# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body Mass Index
HHS: United States Department of Health and Human Services
Kcal: Kilocalories
NESR: Nutrition Evidence Systematic Review
RCT: Randomized Controlled Trial
TEI: Total Energy Intake
USDA: United States Department of Agriculture