# References of the articles included in the systematic review

1 Fagnant HS, Lutz LJ, Nakayama AT, Gaffney-Stomberg E, McClung JP, Karl JP. Breakfast skipping Is associated with Vitamin D deficiency among young adults entering initial military training. J Acad Nutr Diet. Jun 2022;122(6):1114-+. doi:10.1016/j.jand.2021.09.016 34601165
2 Lipsky LM, Nansel TR, Haynie DL, . Diet quality of US adolescents during the transition to adulthood: changes and predictors. Am J Clin Nutr. Jun 1 2017;105(6):1424–1432. doi: 10.3945/ajcn.116.150029 28446498