# Description of the evidence

The body of evidence examining frequency of meals and/or snacking and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans included 2 articles.^1,2^ Both articles examined breakfast consumption. No articles examined other categories of frequency of meals and/or snacking (e.g., number of eating occasions, meal frequency). Included articles are summarized in Table 5, which encompasses each articles’ definition of breakfast consumption, and risk of bias assessments are presented in Table 6.

## Population

Both studies were conducted in the U.S. in very specific populations. One article was conducted in a sample (N=665) of healthy military recruits aged ≥17 years (mean age 21±4 years) from an unnamed cohort.^1^ Another article was conducted in a sample of 10^th^ graders (N=566) from the NEXT Generation Health Study (NEXT Plus subsample).^2^

Both studies reported data on race and/or ethnicity. In the study conducted in military recruits, 70% of participants were White, 18% were Black, 17% were Hispanic, and 12% were reported as “Other”.^1^ In the study conducted in 10^th^ graders, 45% of participants were Non-Hispanic White, 17% were Non-Hispanic Black, 5% were reported as “Other”, and 34% of participants were Hispanic.^2^

Both studies reported data on education as a measure of socioeconomic position. In Fagnant et al^1^, 43% of military recruits had some college education. In Lipsky et al^2^, 65% of parents of included children had some post high school education.

## Intervention/exposure and comparator

Both studies examined self-reported breakfast intake. In Fagnant et al^1^, military recruits were asked “Prior to arrival at initial military training, which meals did you eat on a regular basis (at least 5 times per week)?” at baseline; habitual breakfast skipping was analyzed as a categorical variable (skipped breakfast ≥3 days per week versus no breakfast skipping). In Lipsky et al^2^, 10^th^ graders were asked “How often do you usually have breakfast (more than a glass of milk or fruit juice)?” at baseline and annually for 4 years; breakfast was analyzed as a continuous variable (i.e., days per week).

## Outcome

Both studies examined Healthy Eating Index (HEI)-2010 to reflect adherence to the 2010 Dietary Guidelines for Americans and used 3 nonconsecutive 24-hour diet recalls to assess diet quality. Follow-up duration was 8 to 12 weeks in the study on military recruits^1^ and 4 years in the study on 10^th^ graders^2^.

## Synthesis of the evidence

The body of evidence only included 2 articles, which may be because the review was limited to articles examining diet quality using HEI (which assesses alignment with the Dietary Guidelines for Americans). Both studies examined breakfast. One study in a national cohort of 10th graders reported that a higher weekly breakfast frequency was associated with higher HEI-2010 scores 4 years later.^2^ One study in young adults entering initial military training found that habitually eating breakfast was associated with decreased HEI-2010 scores at 8 to 12 weeks post-training follow-up compared to not eating breakfast ≥3 days a week.^1^ No studies exclusively enrolled an older adult population and no studies examined other categories of frequency of meals and/or snacking (e.g., number of eating occasions, meal frequency).

## Conclusion statement and grade

The Committee was not able to develop a conclusion statement^*^ to answer the question, “What is the relationship between frequency of meals and/or snacking and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans?” based on their review of the body of evidence examining frequency of meals and/or snacking and diet quality as measured by the Healthy Eating Index (Table 4). While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, there were too few studies to thoroughly evaluate publication bias and it is unknown if the influence of publication bias contributed to the lack of articles available for inclusion in this body of evidence.

Table 4 Conclusion statement and grade for frequency of meals and/or snacking and consuming a dietary pattern that is better aligned with the Dietary Guidelines for Americans

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking and consuming a dietary pattern that is better aligned with the Dietary Guidelines for Americans because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 2 articles: both prospective cohort studies
Rationale | There is not enough evidence available to answer this question. Two included articles assessed breakfast and no articles with other categories of frequency of meals were included. The articles had inconsistent results and were in very specific populations:; - 10th graders; - military recruits

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on frequency of meals and/or snacking and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans.

1. Develop and support prospective and/or experimental research that examines the relationship between frequency of meals and/or snacking and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans and other diet indexes that assess similar concepts.
2. Include details about what foods were consumed and their quality by study participants when reporting results related to frequency of meals and/or snacking and diet quality which includes target populations reflective of the geographical, racial, and socioeconomic diversity in the United States.
3. Develop definitions of eating occasions, meals, and snacks as well as frameworks and reporting standards to be used consistently in research in order to increase comparability across studies and aid in the development of guidance around this topic.
4. Support research with funding from Federal and other funding agencies that provides information on types, frequency, timing, and size of meals and/or snacks in order to increase the accuracy and precision of the assessment of meal and snack frequency patterns and the ability to assess the combined and independent effects of frequency and timing of eating.
5. Provide consistency in the operational definition of frequency across studies when developing the comparisons to be examined in articles (e.g., categories of frequency comparisons vs. continuous frequency).
6. Explore all different meals and snack frequency patterns as a 24-hour eating behavior rather than isolating a meal or a snack and consider longer intervention period and follow-up.
7. Conduct studies that have enough follow up to understand the long-term impact of meals/snacks frequency patterns on dietary quality.
8. Continue to evaluate dietary quality using current validated tools (e.g., HEI) over a longer period of time and also develop and validate other methods to assess diet quality, specifically for diverse populations.

Table 5 Evidence examining the relationship between frequency of meals and/or snacking and consuming a dietary pattern that is better aligned with the Dietary Guidelines for Americans^a^

Study and Population Characteristics | Exposure, Comparator, and Outcome(s) | Results and Summary of Findings | Confounding and Study Limitations
Fagnant, 2022^1^; PCS, U.S.; Analytic N=665; Study objective: To determine whether breakfast skipping is associated with odds of Vitamin D deficiency among recruits entering initial military training, and whether diet quality or vitamin D intake mediate those associations. This paper reports an analysis that examines the relationship between breakfast consumption and HEI score.; Participant characteristics at baseline: Healthy military recruits aged ≥17y; - Age: Mean (SD): 21 (4)y; - Female: 45%; - Race and/or ethnicity: White: 70%; Black: 18%; Other: 12%; Hispanic: 17%; - Socioeconomic position: Some college: 43%, No college: 57%; - Anthropometry: Mean BMI ~24.3 kg/m^2^; - Physical activity: 71% >5 times/wk; - Diet quality: HEI, Mean (SD): 54.1 (10.8); breakfast skipping vs 59.5 (12.5) no breakfast skipping, p<0.05; - Smoking: 71% never, 29% current/former; - TEI: NR; - Usual diet at baseline: 46% skip breakfast ≥3 times/wk; Excluded from study or analysis: Those selfidentifying as pregnant, breastfeeding, or allergic to any nutrient component used in the study interventions | Exposure:; Habitual breakfast skipping (i.e., skipped breakfast ≥3 days/wk) vs no breakfast skipping; Assessment methods and timing:; - Self-reported: “Prior to arrival at initial military training, which meals did you eat on a regular basis (at least 5 times per week)?” Recruits who answered “no” for breakfast were categorized as habitual breakfast skippers.; - At baseline (pre-training); Outcomes and assessment methods:; - At baseline (pre-training), and 8-12wk follow-up (post-training); - HEI-2010 (range 0-100; reflects adherence to 2010 Dietary Guidelines for Americans); total scores calculated from block FFQ using simple HEI scoring algorithm method. | [underlined: Change in HEI-2010 total score], Mean (95% CI); Breakfast skipping (n=292): 9.7 (8.2, 11.1) No breakfast skipping (n=373): 5.4 (4.1, 6.8) p<0.001 | Model adjustments:; - TEI: no; - Key confounders: diet quality; - Other: none; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, physical activity, smoking; - Exposure data only assessed at baseline leading to a concern that changes in exposure status occurred over 8-12wk f/u; - High attrition rate/missing data; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding: US Army Medical Research and Development Command, Military Operational Medicine Research Program
Lipsky, 2017^2^; PCS, NEXT Generation Health Study (NEXT Plus subsample), U.S.; Analytic N=566; Study objective: To examine behavioral correlates and baseline predictors of diet quality over the transition to adulthood in a diverse national cohort of U.S. 10th graders. This paper reports the results of analysis that examines the relationship between breakfast frequency and HEI.; Participant characteristics at baseline: National cohort of 10th graders; - Age: Mean: 16.5y; - Female: 55%; - Race and/or ethnicity: Non-Hispanic White: 45%; Non-Hispanic Black: 17%; Other: 5%; Hispanic: 34%; - Socioeconomic position: Parent education: 36% ≤ high school graduate/GED; 41% some post high school, 24% ≥college degree; Family Affluence Score (1-5): Mean 5; - Anthropometry: Weight status based on BMI%: 51% normal weight, 23% overweight, 26% obesity; - Physical activity: MVPA, Mean 0.4 hr/d; - Diet quality: HEI, Mean (SE): 44.07 (0.53); - Smoking: NR; - TEI: NR; - Usual diet at baseline: Breakfast: Mean (SE) 4.6 (0.1) days/wk; Excluded from study or analysis: Those with blood conditions associated with increased bleeding risk | Exposure:; Breakfast frequency during the past week (days/wk); Assessment methods and timing:; - Self-reported: “How often do you usually have breakfast (more than a glass of milk or fruit juice)?” Participants reported separately for weekdays (response options included never and 1, 2, 3, 4, and 5 d) and weekend days [response options included never, 1 d of the weekend (Saturday or Sunday), and both weekend days (Saturday and Sunday)]. Responses were converted to represent the number of days per week by using the midpoint of the response option ranges (e.g., 1-2 d/wk was converted to 1.5).; - At baseline (10th grade), and annually for 4y; Outcomes and assessment methods:; - At baseline (10th grade), and annually for 4y; - HEI-2010 (range 0-100; reflects adherence to 2010 Dietary Guidelines for Americans) calculated from diet recall data. Participants completed 3 nonconsecutive 24hr diet recalls. | [underlined: HEI-2010 total score] based on weekly breakfast frequency, β (SE); 0.69 (0.13); p<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, diet quality; - Other: time (wave); time-varying height; Limitations:; - Did not account for key confounders: physical activity; - No preregistered data analysis plan; - Water/Beverages were not accounted for in exposure assessment; - Did not adjust for TEI; Funding: NICHD; NHLBI; NIAAA; MCHB with supplemental support from NIDA

Table 6 Risk of bias for observational studies examining frequency of meals and/or snacking and consuming a dietary pattern that is better aligned with the Dietary Guidelines for Americans^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Fagnant, 2022 ^1^ | VERY HIGH | SOME CONCERNS | LOW | HIGH | HIGH | LOW | SOME CONCERNS | VERY HIGH
Lipsky, 2017 ^2^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

a Abbreviations: BMI: body mass index; d: day(s); f/u: follow up; HEI: healthy eating index; PCS: prospective cohort study; MVPA: moderate to vigorous physical activity; SD: standard deviation; SE: standard error; TEI: total energy intake; wk: week(s); y: year(s)

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602.)