# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 3 systematic reviews assessing the relationship between the frequency of meals and snacking and three distinct outcomes (energy intake^†^; alignment with the Dietary Guidelines for Americans (diet quality); and growth, body composition, and risk of obesity^‡^); however, this report is specific to the outcome of alignment with the Dietary Guidelines for Americans (diet quality). The literature search (Appendix 2) yielded 31,399 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 27,732 titles, 2,821 abstracts, and 704 full-texts articles. Reasons for full-text exclusion are in Appendix 3. No additional articles were identified from the manual search. The body of evidence on frequency of meals and/or snacking and alignment with the Dietary Guidelines for Americans (diet quality) included 2 articles.^1,2^

Figure 2 Literature search and screen flowchart

Literature search and screen flowchart The literature search in PubMed, Embase, Cochrane, and CINAHL retrieved 31,399 records after removing duplicates. No articles were found with manual search methods. 27,732 titles, 2821 abstracts, and 704 full-texts were excluded. 142 articles were included across the 3 systematic reviews examining frequency of meals and/or snacking. Of these, 2 articles were included in the systematic review on diet quality.

† Andres A, Giovannucci E, Fisher JO, . Frequency of Meals and/or Snacking and Energy Intake: A Systematic Review. 2025. 10.52570/NESR.DGAC2025.SR10

‡ Palacios C, Raynor HA, Anderson CAM, . Frequency of Meals and/or Snacking and Growth, Body Composition, and Risk of Obesity: A Systematic Review. 2025. 10.52570/NESR.DGAC2025.SR16