# Plain language summary

## What is the question?

The question is: What is the relationship between frequency of meals and/or snacking and consuming a dietary pattern that is aligned with the Dietary Guidelines for Americans? The populations of interest for this question include young children, children, and adolescents (1 up to 19 years), and adults and older adults (19 years and older).

## Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

## How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

## What is the answer to the question?

A conclusion statement cannot be drawn about the relationship between frequency of meals and/or snacking and consuming a dietary pattern that is better aligned with the Dietary Guidelines for Americans because there is not enough evidence available.

## How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and May 2023.