# Acknowledgements

The Committee members were involved in: establishing all aspects of the protocol, which presented the plan for how they would examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; deliberating on the body of evidence for each question; and writing and grading the conclusion statements. The NESR team, with assistance from Federal staff from HHS and USDA (Meghan Adler, MS, RDN; Carolyn Chung, PhD; Dana DeSilva, PhD, RD; Rachel Inman, RD; Sarah Karp, MNSP, RD, LDN; Emily Levin, MPH, RDN; Chinwe Obudulu, MS, RD, LD; Elizabeth Rahavi, RD) and Project Leadership (Janet de Jesus, MS, RD; Eve Stoody, PhD), supports the Committee by facilitating, executing, and documenting the work necessary to ensure the reviews are completed in accordance with NESR methodology.

The Committee and NESR staff thank staff from the National Institutes of Health (NIH) for coordinating the peer review of this systematic review, and the peer reviewers for their time and expertise.

The Committee and NESR staff thank other members of the NESR team (Brittany Kingshipp, PhD; Allison Webster, PhD, RD) for providing support during development of the review protocol.