# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 6 Articles excluded after full-text screening

| Citation | Rationale
1 | Skipping meals might increase the risk of metabolic syndrome. Nature Clinical Practice Endocrinology and Metabolism. 2008. 4:532-533. doi:10.1038/ncpendmet0934. | Study design; Publication status
2 | Virchow and the Weight-loss Breakfast. Orthopedics. 2009. 32:397. doi:10.3928/01477447-20090511-03. | Study design
3 | Abdullatif, M, Alabady, K, Altheeb, et al. Prevalence of Overweight, Obesity, and Dietary Behaviors among Adolescents in Dubai Schools: A Complex Design Survey 2019. Dubai Medical Journal. 2022. 5:1-9. doi:10.1159/000519863. | Study design
4 | Abildso, CG, Schmid, O, Byrd, et al. Predictors of weight loss maintenance following an insurance-sponsored weight management program. J Obes. 2014. 2014:736080. doi:10.1155/2014/736080. | Study design
5 | Agras, WS, Hammer, LD, McNicholas, et al. Risk factors for childhood overweight: a prospective study from birth to 9.5 years. J Pediatr. 2004. 145:20-5. doi:10.1016/j.jpeds.2004.03.023. | Intervention/Exposure
6 | Ahc, Media. Time-Restricted Eating, Weight Loss, and Metabolism. Internal Medicine Alert. 2021. 43:1-3. | Intervention/Exposure; Publication status
7 | Ahmad, Norliza, Shariff, Zalilah Mohd, Mukhtar, et al. Family-based intervention using face-to-face sessions and social media to improve Malay primary school children’s adiposity: a randomized controlled field trial of the Malaysian REDUCE programme. Nutr J. 2018. 17:N.PAG-N.PAG. doi:10.1186/s12937-018-0379-1. | Intervention/Exposure
8 | Ainscough, KM, Kennelly, MA, Lindsay, et al. An observational analysis of meal patterns in overweight and obese pregnancy: exploring meal pattern behaviours and the association with maternal and fetal health measures. Ir J Med Sci. 2020. 189:585-594. doi:10.1007/s11845-019-02099-0. | Outcome
9 | Aizawa, M, Murakami, K, Takahashi, et al. Association between frequency of breakfast intake before and during pregnancy and infant birth weight: the Tohoku Medical Megabank Project Birth and Three-Generation Cohort Study. BMC Pregnancy Childbirth. 2023. 23:268. doi:10.1186/s12884-023-05603-8. | Outcome
10 | Aksungar, FB, Topkaya, AE, Akyildiz, et al. Interleukin-6, C-reactive protein and biochemical parameters during prolonged intermittent fasting. Ann Nutr Metab. 2007. 51:88-95. doi:10.1159/000100954. | Intervention/Exposure
11 | Aksungar, Fehime, Sarikaya, M, Coskun, et al. Comparison of intermittent fasting versus caloric restriction in obese subjects: A two year follow-up. Journal of Nutrition, Health & Aging. 2017. 21:681-685. doi:10.1007/s12603-016-0786-y. | Intervention/Exposure
12 | Al-Ardhi, GH, Ibraheem, NJ, Al-Maamory, et al. Comparison of some physiological parameters determined by timing consumption of breakfast meal among adult women. Indian Journal of Forensic Medicine and Toxicology. 2021. 15:2394-2396. doi:10.37506/ijfmt.v15i3.15670. | Study design; Intervention/Exposure
13 | Albertson, AM, Affenito, SG, Bauserman, et al. The relationship of ready-to-eat cereal consumption to nutrient intake, blood lipids, and body mass index of children as they age through adolescence. J Am Diet Assoc. 2009. 109:1557-65. doi:10.1016/j.jada.2009.06.363. | Intervention/Exposure
14 | Aldhoon-Hainerová I, Hainer V, Zamrazilová H. Impact of dietary intake, lifestyle and biochemical factors on metabolic health in obese adolescents. Nutr Metab Cardiovasc Dis. 2017;27(8):703-710. doi:10.1016/j.numecd.2017.05.002 | Study design
15 | Alencar, MK, Beam, JR, McCormick, et al. Increased meal frequency attenuates fat-free mass losses and some markers of health status with a portion-controlled weight loss diet. Nutr Res. 2015. 35:375–383. doi:10.1016/j.nutres.2015.03.003. | Outcome; Duration
16 | Alexy, U, Wicher, M, Kersting, et al. Breakfast trends in children and adolescents: frequency and quality. Public Health Nutr. 2010. 13:1795-802. doi:10.1017/s1368980010000091. | Intervention/Exposure; Outcome
17 | Alhussain, MH, Macdonald, IA, Taylor, et al. Irregular meal-pattern effects on energy expenditure, metabolism, and appetite regulation: a randomized controlled trial in healthy normal-weight women. Am J Clin Nutr. 2016. 104:21-32. doi:10.3945/ajcn.115.125401. | Outcome; Duration
18 | Alinezhad-Namaghi, Maryam, Eslami, Saeid, Nematy, et al. Intermittent Fasting During Ramadan and Its Effects in Individuals With Metabolic Syndrome. Nutr Today. 2019. 54:159-164. doi:10.1097/NT.0000000000000351. | Intervention/Exposure
19 | Allirot X, Saulais L, Seyssel K, et al. An isocaloric increase of eating episodes in the morning contributes to decrease energy intake at lunch in lean men. Physiol Behav. 2013;110-111:169-178. doi:10.1016/j.physbeh.2013.01.009 | Intervention/Exposure
20 | Allirot, X, Seyssel, K, Saulais, et al. Effects of a breakfast spread out over time on the food intake at lunch and the hormonal responses in obese men. Physiol Behav. 2014. 127:37-44. doi:10.1016/j.physbeh.2014.01.004. | Intervention/Exposure
21 | Allison, KC, Hopkins, CM, Ruggieri, et al. Prolonged, Controlled Daytime versus Delayed Eating Impacts Weight and Metabolism. Curr Biol. 2021. 31:650-657.e3. doi:10.1016/j.cub.2020.10.092. | Intervention/Exposure; Comparator
22 | Almeneessier, A, Bahammam, A, Sharif, et al. The influence of intermittent fasting on the circadian pattern of melatonin while controlling for caloric intake, energy expenditure, light exposure, and sleep schedules: A preliminary report. Ann Thorac Med. 2017. 12:183-190. doi:10.4103/atm.ATM_15_17. | Intervention/Exposure
23 | Almeneessier, AS, BaHammam, AA, Alzoghaibi, et al. The effects of diurnal intermittent fasting on proinflammatory cytokine levels while controlling for sleep/wake pattern, meal composition and energy expenditure. PLoS One. 2019. 14:e0226034. doi:10.1371/journal.pone.0226034. | Intervention/Exposure
24 | Almoosawi, S, Prynne, CJ, Hardy, et al. Time-of-day and nutrient composition of eating occasions: prospective association with the metabolic syndrome in the 1946 British birth cohort. Int J Obes (Lond). 2013. 37:725-31. doi:10.1038/ijo.2012.103. | Intervention/Exposure
25 | Almoosawi, S, Prynne, CJ, Hardy, et al. Time-of-day of energy intake: association with hypertension and blood pressure 10 years later in the 1946 British Birth Cohort. J Hypertens. 2013. 31:882-92. doi:10.1097/HJH.0b013e32835ecc06. | Intervention/Exposure; Outcome
26 | Alqaoud, N, Al-Jawaldeh, A, Al-Anazi, et al. Trend and Causes of Overweight and Obesity among Pre-School Children in Kuwait. Children (Basel). 2021. 8:. doi:10.3390/children8060524 . | Study design
27 | Al-Rawi, N, Madkour, M, Jahrami, et al. Effect of diurnal intermittent fasting during Ramadan on ghrelin, leptin, melatonin, and cortisol levels among overweight and obese subjects: A prospective observational study. PLoS One. 2020. 15:e0237922. doi:10.1371/journal.pone.0237922. | Intervention/Exposure
28 | Alsharairi, NA, Somerset, SM. Skipping breakfast in early childhood and its associations with maternal and child BMI: a study of 2-5-year-old Australian children. Eur J Clin Nutr. 2016. 70:450-5. doi:10.1038/ejcn.2015.184. | Intervention/Exposure; Outcome
29 | Alviso-Orellana, C, Estrada-Tejada, D, Carrillo-Larco, et al. Sweetened beverages, snacks and overweight: findings from the Young Lives cohort study in Peru. Public Health Nutr. 2018. 21:1627-1633. doi:10.1017/s1368980018000320. | Intervention/Exposure
30 | Alwattar, AY, Thyfault, JP, Leidy, et al. The effect of breakfast type and frequency of consumption on glycemic response in overweight/obese late adolescent girls. Eur J Clin Nutr. 2015. 69:885-90. doi:10.1038/ejcn.2015.12. | Outcome
31 | Amosa, T, Rush, E, Plank, et al. Frequency of eating occasions reported by young New Zealand Polynesian and European women. Pac Health Dialog. 2001. 8:59-65. | Study design
32 | Andersson I, Lennernäs M, Rössner S. Meal pattern and risk factor evaluation in one-year completers of a weight reduction program for obese men - the ‘Gustaf’ study. J Intern Med. 2000;247(1):30-38. doi:10.1046/j.1365-2796.2000.00569.x | Intervention/Exposure
33 | Andrade, Lucia, Zazpe, Itziar, Santiago, et al. Ten-Year Changes in Healthy Eating Attitudes in the SUN Cohort. J Am Coll Nutr. 2017. 36:319-329. doi:10.1080/07315724.2016.1278566. | Intervention/Exposure; Outcome
34 | Andrews, Lisa. Daily Breakfast Brings Weight Loss. Communicating Food for Health. 2017. Pg. 7-8. | Study design
35 | Antoni, R, Johnston, KL, Collins, et al. Intermittent v. continuous energy restriction: differential effects on postprandial glucose and lipid metabolism following matched weight loss in overweight/obese participants. Br J Nutr. 2018. 119:507-516. doi:10.1017/s0007114517003890 . | Intervention/Exposure
36 | Antoni, R, Robertson, TM, Robertson, et al. A pilot feasibility study exploring the effects of a moderate time-restricted feeding intervention on energy intake, adiposity and metabolic physiology in free-living human subjects. J Nutr Sci. 2018. 7:. doi:10.1017/jns.2018.13. | Intervention/Exposure
37 | Arabshahi, S, Lahmann, PH, Hughes, et al. Dietary behaviours, weight loss attempts and change in waist circumference: 15-year longitudinal study in Australian adults. Asia Pac J Clin Nutr. 2017. 26:657-664. doi:10.6133/apjcn.062016.04. | Intervention/Exposure
38 | Arciero, PJ, Ormsbee, MJ, Gentile, et al. Increased protein intake and meal frequency reduces abdominal fat during energy balance and energy deficit. Obesity (Silver Spring). 2013. 21:1357-66. doi:10.1002/oby.20296. | Outcome; Duration
39 | Ardolino, Alyssa. Snacking Series: Do Snacks Lead to Weight Gain?. Food Insight. 2018. 3-3. | Study design
40 | Arenaza L, Muñoz-Hernández V, Medrano M, et al. Association of Breakfast Quality and Energy Density with Cardiometabolic Risk Factors in Overweight/Obese Children: Role of Physical Activity. Nutrients. 2018;10(8):1066. Published 2018 Aug 10. doi:10.3390/nu10081066 | Study design; Intervention/Exposure
41 | Asghari, G, Yuzbashian, E, Mirmiran, et al. Prediction of metabolic syndrome by a high intake of energy-dense nutrient-poor snacks in Iranian children and adolescents. Pediatr Res. 2016. 79:697-704. doi:10.1038/pr.2015.270. | Intervention/Exposure
42 | Ashwell, M, Hunty, A. How does breakfast help manage bodyweight?. Nutrition Bulletin. 2012. 37:395-397. doi:10.1111/j.1467-3010.2012.01994.x. | Study design
43 | Ask, AS, Hernes, S, Aarek, et al. Changes in dietary pattern in 15 year old adolescents following a 4 month dietary intervention with school breakfast-a pilot study. Nutr J. 2006. 5:33. doi:10.1186/1475-2891-5-33. | Intervention/Exposure
44 | Azadbakht, L, Haghighatdoost, F, Feizi, et al. Breakfast eating pattern and its association with dietary quality indices and anthropometric measurements in young women in Isfahan. Nutrition. 2013. 29:420-5. doi:10.1016/j.nut.2012.07.008. | Study design
45 | Özcan BA, Yeşı̇lkaya B, Yaldiz N, Pehlı̇van M. Factors affecting diet quality in adolescents: the effect of sociodemographic characteristics and meal consumption. Progress in Nutrition. 2020;22(4):e2020094-e2020094. doi:https://doi.org/10.23751/pn.v22i4.10927 | Study design
46 | Bachman, JL, Phelan, S, Wing, et al. Eating frequency is higher in weight loss maintainers and normal-weight individuals than in overweight individuals. J Am Diet Assoc. 2011. 111:1730-4. doi:10.1016/j.jada.2011.08.006. | Study design
47 | Bailey, BW, Sullivan, DK, Kirk, et al. Dietary predictors of visceral adiposity in overweight young adults. Br J Nutr. 2010. 103:1702-5. doi:10.1017/s0007114509993771. | Study design; Intervention/Exposure
48 | Balieiro, LCT, Gontijo, CA, Marot, et al. Is chronotype associated with dietary intake and weight gain during pregnancy? A prospective and longitudinal study. Nutrition. 2022. 94:. doi:10.1016/j.nut.2021.111530. | Intervention/Exposure
49 | Ball, K, Brown, W, Crawford, et al. Who does not gain weight? Prevalence and predictors of weight maintenance in young women. Int J Obes Relat Metab Disord. 2002. 26:1570-8. doi:10.1038/sj.ijo.0802150. | Intervention/Exposure
50 | Bandín C, Scheer FA, Luque AJ, et al. Meal timing affects glucose tolerance, substrate oxidation and circadian-related variables: A randomized, crossover trial. Int J Obes (Lond). 2015;39(5):828-833. doi:10.1038/ijo.2014.182 | Intervention/Exposure; Comparator
51 | Bantle, AE, Lau, KJ, Wang, et al. Time-restricted eating did not alter insulin sensitivity or Î^2^-cell function in adults with obesity: A randomized pilot study. Obesity (Silver Spring). 2023. 31 Suppl 1:108-115. doi:10.1002/oby.23620. | Intervention/Exposure
52 | Barba, G, Troiano, E, Russo, et al. Total fat, fat distribution and blood pressure according to eating frequency in children living in southern Italy: the ARCA project. Int J Obes (Lond). 2006. 30:1166-9. doi:10.1038/sj.ijo.0803257. | Study design
53 | Baron, KG, Reid, KJ, Kern, et al. Role of sleep timing in caloric intake and BMI. Obesity (Silver Spring). 2011. 19:1374-81. doi:10.1038/oby.2011.100. | Intervention/Exposure
54 | Barone Gibbs B, Kinzel LS, Pettee Gabriel K, Chang YF, Kuller LH. Short- and long-term eating habit modification predicts weight change in overweight, postmenopausal women: results from the WOMAN study. J Acad Nutr Diet. 2012;112(9):1347-1355.e2. doi:10.1016/j.jand.2012.06.012 | Intervention/Exposure
55 | Basdeki, ED, Argyris, AA, Efthymiou, et al. Systematic Breakfast Consumption of Medium-Quantity and High-Quality Food Choices Is Associated with Better Vascular Health in Individuals with Cardiovascular Disease Risk Factors. Nutrients. 2023. 15:. doi:10.3390/nu15041025. | Study design
56 | Basterra-Gortari FJ, Bes-Rastrollo M, Pardo-Fernández M, Forga L, Martinez JA, Martínez-González MA. Changes in weight and physical activity over two years in Spanish alumni. Med Sci Sports Exerc. 2009;41(3):516-522. doi:10.1249/MSS.0b013e318188607c | Intervention/Exposure
57 | Batista-Jorge, GC, Barcala-Jorge, AS, Oliveira Dias, et al. Nutritional Status Associated to Skipping Breakfast in Brazilian Health Service Patients. Ann Nutr Metab. 2016. 69:31-40. doi:10.1159/000447363. | Study design
58 | Bawaked, RA, Gomez, SF, Homs, et al. Association of eating behaviors, lifestyle, and maternal education with adherence to the Mediterranean diet in Spanish children. Appetite. 2018. 130:279-285. doi:10.1016/j.appet.2018.08.024. | Outcome
59 | Beaudry, KM, Ludwa, IA, Thomas, et al. First-year university is associated with greater body weight, body composition and adverse dietary changes in males than females. PLoS One. 2019. 14:e0218554. doi:10.1371/journal.pone.0218554. | Intervention/Exposure; Outcome
60 | Beaulieu, K, Casanova, N, Oustric, et al. Matched Weight Loss Through Intermittent or Continuous Energy Restriction Does Not Lead To Compensatory Increases in Appetite and Eating Behavior in a Randomized Controlled Trial in Women with Overweight and Obesity. J Nutr. 2020. 150:623-633. doi:10.1093/jn/nxz296. | Intervention/Exposure
61 | Beaulieu, K, Oustric, P, Alkahtani, et al. Impact of Meal Timing and Chronotype on Food Reward and Appetite Control in Young Adults. Nutrients. 2020. 12:. doi:10.3390/nu12051506. | Intervention/Exposure; Outcome
62 | Beşoluk Ş. Association of dietary patterns with circadian preference, sleep and personality in high school students. Biological Rhythm Research. Published online January 17, 2018:1-13. doi:10.1080/09291016.2018.1427601 | Study design; Outcome
63 | Befort, CA, Stewart, EE, Smith, et al. Weight maintenance, behaviors and barriers among previous participants of a university-based weight control program. Int J Obes (Lond). 2008. 32:519-26. doi:10.1038/sj.ijo.0803769. | Study design; Intervention/Exposure
64 | Belderson, P, Harvey, I, Kimbell, et al. Does breakfast-club attendance affect schoolchildren’s nutrient intake? A study of dietary intake at three schools. Br J Nutr. 2003. 90:1003-6. doi:10.1079/bjn20031011. | Study design; Intervention/Exposure
65 | Bellisle, F. Impact of the daily meal pattern on energy balance. Scandinavian Journal of Nutrition. 2004. 48:114-118. doi:10.1080/11026480410000454. | Study design
66 | Benton, D, Jarvis, M. The role of breakfast and a mid-morning snack on the ability of children to concentrate at school. Physiol Behav. 2007. 90:382-5. doi:10.1016/j.physbeh.2006.09.029. | Outcome
67 | Berendsen, M, Boss, M, Smits, et al. Chrono-Nutrition and Diet Quality in Adolescents with Delayed Sleep-Wake Phase Disorder. Nutrients. 2020. 12:. doi:10.3390/nu12020539. | Intervention/Exposure
68 | Berentzen, NE, Smit, HA, van Rossem, et al. Screen time, adiposity and cardiometabolic markers: mediation by physical activity, not snacking, among 11-year-old children. Int J Obes (Lond). 2014. 38:1317-23. doi:10.1038/ijo.2014.110. | Intervention/Exposure
69 | Berge, JericaM, Wall, Melanie, Hsueh, et al. The protective role of family meals for youth obesity: 10-year longitudinal associations. J Pediatr. 2015. 166:296-301. doi:10.1016/j.jpeds.2014.08.030. | Intervention/Exposure
70 | Berge, JM, MacLehose, RF, Loth, et al. Family meals. Associations with weight and eating behaviors among mothers and fathers. Appetite. 2012. 58:1128-35. doi:10.1016/j.appet.2012.03.008. | Intervention/Exposure
71 | Bernabe-Ortiz, A, Mendoza-Quispe, D, Jimenez, et al. Quantifying the childhood and adolescent overnutrition attributable to specific risk factors: The Young Lives Study in Peru. Pediatr Obes. 2023. 18:e13002. doi:10.1111/ijpo.13002. | Intervention/Exposure
72 | Bes-Rastrollo M, Basterra-Gortari FJ, Sánchez-Villegas A, Marti A, Martínez JA, Martínez-González MA. A prospective study of eating away-from-home meals and weight gain in a Mediterranean population: the SUN (Seguimiento Universidad de Navarra) cohort. Public Health Nutr. 2010;13(9):1356-1363. doi:10.1017/S1368980009992783 | Intervention/Exposure
73 | Bes-Rastrollo M, Sánchez-Villegas A, Gómez-Gracia E, Martínez JA, Pajares RM, Martínez-González MA. Predictors of weight gain in a Mediterranean cohort: the Seguimiento Universidad de Navarra Study 1. Am J Clin Nutr. 2006;83(2):362-395. doi:10.1093/ajcn/83.2.362 | Study design; Intervention/Exposure
74 | Beyerlein, A, Fahrmeir, L, Mansmann, et al. Alternative regression models to assess increase in childhood BMI. BMC Med Res Methodol. 2008. 8:59. doi:10.1186/1471-2288-8-59. | Study design
75 | Bhutani, S, vanDellen, MR, Cooper, et al. Longitudinal Weight Gain and Related Risk Behaviors during the COVID-19 Pandemic in Adults in the US. Nutrients. 2021. 13:. doi:10.3390/nu13020671. | Study design; Outcome
76 | Bhutani, S, Wells, N, Finlayson, et al. Change in eating pattern as a contributor to energy intake and weight gain during the winter holiday period in obese adults. Int J Obes (Lond). 2020. 44:1586-1595. doi:10.1038/s41366-020-0562-2. | Intervention/Exposure
77 | Bin Naharudin, MN, Yusof, A, Shaw, et al. Breakfast Omission Reduces Subsequent Resistance Exercise Performance. J Strength Cond Res. 2019. 33:1766-1772. doi:10.1519/jsc.0000000000003054. | Outcome
78 | Bjerre, N, Holm, L, Veje, et al. What happens after a weight loss intervention? A qualitative study of drivers and challenges of maintaining time-restricted eating among people with overweight at high risk of type 2 diabetes. Appetite. 2022. 174:106034. doi:10.1016/j.appet.2022.106034. | Study design; Intervention/Exposure; Outcome
79 | Black, MM, Papas, MA, Bentley, et al. Overweight adolescent African-American mothers gain weight in spite of intentions to lose weight. J Am Diet Assoc. 2006. 106:80-7. doi:10.1016/j.jada.2005.09.049. | Intervention/Exposure
80 | Bo, Liu, Hutchison, AmyT, Thompson, et al. Effects of Intermittent Fasting or Calorie Restriction on Markers of Lipid Metabolism in Human Skeletal Muscle. J Clin Endocrinol Metab. 2021. 106:e1389-e1399. doi:10.1210/clinem/dgaa707. | Intervention/Exposure
81 | Bo, S, De Carli, L, Venco, et al. Impact of snacking pattern on overweight and obesity risk in a cohort of 11- to 13-year-old adolescents. J Pediatr Gastroenterol Nutr. 2014. 59:465-71. doi:10.1097/mpg.0000000000000453. | Study design
82 | Bo, S, Fadda, M, Castiglione, et al. Is the timing of caloric intake associated with variation in diet-induced thermogenesis and in the metabolic pattern? A randomized cross-over study. Int J Obes (Lond). 2015. 39:1689–1695. doi:10.1038/ijo.2015.138. | Intervention/Exposure; Comparator
83 | Bolze, C, Gray-Donald, K, Dugas, et al. Predictors of Weight Loss in Young Adults. Child Obes. 2015. 11:541-8. doi:10.1089/chi.2014.0160. | Intervention/Exposure
84 | Borg, P, Fogelholm, M, Kukkonen-Harjula, et al. Food selection and eating behaviour during weight maintenance intervention and 2-y follow-up in obese men. Int J Obes Relat Metab Disord. 2004. 28:1548-54. doi:10.1038/sj.ijo.0802790. | Intervention/Exposure
85 | Boucher, AB, Adesanya, EA, Owei, et al. Dietary habits and leisure-time physical activity in relation to adiposity, dyslipidemia, and incident dysglycemia in the pathobiology of prediabetes in a biracial cohort study. Metabolism. 2015. 64:1060-7. doi:10.1016/j.metabol.2015.05.015. | Intervention/Exposure
86 | Boynton, A, Neuhouser, ML, Sorensen, et al. Predictors of diet quality among overweight and obese postmenopausal women. J Am Diet Assoc. 2008. 108:125-30. doi:10.1016/j.jada.2007.10.037. | Study design; Intervention/Exposure
87 | Brady, AJ, Langton, HM, Mulligan, et al. Effects of 8 wk of 16:8 Time-restricted Eating in Male Middle- and Long-Distance Runners. Med Sci Sports Exerc. 2021. 53:633-642. doi:10.1249/mss.0000000000002488. | Intervention/Exposure
88 | Brikou, D, Zannidi, D, Karfopoulou, et al. Breakfast consumption and weight-loss maintenance: results from the MedWeight study. Br J Nutr. 2016. 115:2246-51. doi:10.1017/s0007114516001550. | Study design
89 | Bruening, M, Larson, N, Story, et al. Predictors of adolescent breakfast consumption: longitudinal findings from Project EAT. J Nutr Educ Behav. 2011. 43:390-5. doi:10.1016/j.jneb.2011.02.016. | Intervention/Exposure; Outcome
90 | Burgess-Champoux, TL, Larson, N, Neumark-Sztainer, et al. Are family meal patterns associated with overall diet quality during the transition from early to middle adolescence?. J Nutr Educ Behav. 2009. 41:79-86. doi:10.1016/j.jneb.2008.03.113. | Intervention/Exposure; Outcome
91 | Buscemi, J, Berlin, KS, Rybak, et al. Health Behavior and Weight Changes Among Ethnic and Racial Minority Preschoolers and Their Parents: Associations Across 1 Year. J Pediatr Psychol. 2016. 41:777-85. doi:10.1093/jpepsy/jsv165. | Intervention/Exposure
92 | Buyken AE, Trauner K, Günther AL, Kroke A, Remer T. Breakfast glycemic index affects subsequent daily energy intake in free-living healthy children. Am J Clin Nutr. 2007;86(4):980-987. doi:10.1093/ajcn/86.4.980 | Intervention/Exposure
93 | Cachelin, FM, Thomas, C, Vela, et al. Associations between meal patterns, binge eating, and weight for Latinas. Int J Eat Disord. 2017. 50:32-39. doi:10.1002/eat.22580. | Study design
94 | Cahill, LE. About time: eating timing is a complex risk factor for obesity. Am J Clin Nutr. 2021. 113:5-6. doi:10.1093/ajcn/nqaa329. | Study design
95 | Calamaro, CJ, Park, S, Mason, et al. Shortened sleep duration does not predict obesity in adolescents. J Sleep Res. 2010. 19:559-66. doi:10.1111/j.1365-2869.2010.00840.x. | Study design; Intervention/Exposure
96 | Calleja Fernández A, Muñoz Weigand C, Ballesteros Pomar MD, et al. Modificación de los hábitos alimentarios del almuerzo en una población escolar [Changes on dietary habits of the late-breakfast in a school population]. Nutr Hosp. 2011;26(3):560-565. doi:10.1590/S0212-16112011000300019 | Intervention/Exposure; Language
97 | Cameron, JD, Cyr, MJ, Doucet, et al. Increased meal frequency does not promote greater weight loss in subjects who were prescribed an 8-week equi-energetic energy-restricted diet. Br J Nutr. 2010. 103:1098-101. doi:10.1017/s0007114509992984. | Duration
98 | Capaldi, ED, Owens, JQ, Privitera, et al. Isocaloric meal and snack foods differentially affect eating behavior. Appetite. 2006. 46:117-23. doi:10.1016/j.appet.2005.10.008. | Comparator
99 | Carels, RA, Young, KM, Coit, et al. Skipping meals and alcohol consumption. The regulation of energy intake and expenditure among weight loss participants. Appetite. 2008. 51:538-45. doi:10.1016/j.appet.2008.04.006. | Study design
100 | Carew, AS, Mekary, RA, Kirkland, et al. Prospective Study of Skipping Meals to Lose Weight as a Predictor of Incident Type 2 Diabetes With Potential Modification by Cardiometabolic Risk Factors: The Canadian 1995 Nova Scotia Health Survey. Can J Diabetes. 2021. 45:306-312. doi:10.1016/j.jcjd.2020.09.009. | Outcome
101 | Carlson, JA, Crespo, NC, Sallis, et al. Dietary-related and physical activity-related predictors of obesity in children: a 2-year prospective study. Child Obes. 2012. 8:110-5. doi:10.1089/chi.2011.0071. | Intervention/Exposure
102 | Carlson, O, Martin, B, Stote, et al. Impact of reduced meal frequency without caloric restriction on glucose regulation in healthy, normal-weight middle-aged men and women. Metabolism. 2007. 56:1729-34. doi:10.1016/j.metabol.2007.07.018. | Comparator; Outcome; Duration
103 | Carnell, S, Papantoni, A, Grillot, et al. Time of day differences in appetite and gut hormone responses to meal and stress challenges in adults with normal-weight and obesity. Physiol Behav. 2022. 254:113890. doi:10.1016/j.physbeh.2022.113890. | Intervention/Exposure
104 | Carriere, C, Langevin, C, Lamireau, et al. Dietary behaviors as associated factors for overweight and obesity in a sample of adolescents from Aquitaine, France. J Physiol Biochem. 2013. 69:111-8. doi:10.1007/s13105-012-0194-7. | Study design
105 | Chang, Y, Gable, S. Predicting weight status stability and change from fifth grade to eighth grade: the significant role of adolescents’ social-emotional well-being. J Adolesc Health. 2013. 52:448-55. doi:10.1016/j.jadohealth.2012.09.005. | Intervention/Exposure
106 | Chapelot, D, Marmonier, C, Aubert, et al. A role for glucose and insulin preprandial profiles to differentiate meals and snacks. Physiol Behav. 2004. 80:721-31. doi:10.1016/j.physbeh.2003.12.006. | Study design
107 | Chapelot, D, Marmonier, C, Aubert, et al. Consequence of omitting or adding a meal in man on body composition, food intake, and metabolism. Obesity (Silver Spring). 2006. 14:215-27. doi:10.1038/oby.2006.28. | Outcome
108 | Chen, C, Aslani, TV, Rosen, et al. Healthcare shift workers’ temporal habits for eating, sleeping, and light exposure: A multi-instrument pilot study. J Circadian Rhythms. 2020. 18:. doi:10.5334/JCR.199. | Intervention/Exposure
109 | Chen, Chun-Yuan, Hsiao, Yi-Chen. Dual trajectories of breakfast eating and fruit and vegetable intake over a 5-year follow-up period among economically disadvantaged children: Gender differences. Appetite. 2018. 121:41-49. doi:10.1016/j.appet.2017.10.027. | Outcome
110 | Chen, JL, Wall, D, Kennedy, et al. Predictors of increased body mass index in Chinese children. Prog Cardiovasc Nurs. 2007. 22:138-44. doi:10.1111/j.0889-7204.2007.05668.x. | Intervention/Exposure
111 | Cheng, ErikaR, Carroll, AaronE. Offering Breakfast in the Classroom and Children’s Weight Outcomes. . 2019. 173:317-318. doi:10.1001/jamapediatrics.2018.5539. | Study design
112 | Cheng, TS, Loy, SL, Toh, et al. Predominantly nighttime feeding and weight outcomes in infants. Am J Clin Nutr. 2016. 104:380-8. doi:10.3945/ajcn.116.130765. | Population Life Stage; Intervention/Exposure
113 | Chin, SO, Keum, C, Woo, et al. Successful weight reduction and maintenance by using a smartphone application in those with overweight and obesity. Sci Rep. 2016. 6:34563. doi:10.1038/srep34563. | Intervention/Exposure
114 | Chiu, CH, Chen, CH, Wu, et al. 5Â days of time-restricted feeding increases fat oxidation rate but not affect postprandial lipemia: a crossover trial. Sci Rep. 2022. 12:9295. doi:10.1038/s41598-022-13387-8. | Intervention/Exposure
115 | Cho, S, Alberding, J, Sadler, et al. Worksite weight loss program with meal and snack replacement system: twelve-week results. Am J Clin Nutr. 2002. 75:383S. doi: 10.1093/ajcn/75.2.339S | Intervention/Exposure; Publication status
116 | Chow, LS, Manoogian, ENC, Alvear, et al. Time-Restricted Eating Effects on Body Composition and Metabolic Measures in Humans who are Overweight: a Feasibility Study. Obesity (Silver Spring). 2020. 28:860–869. doi:10.1002/oby.22756. | Intervention/Exposure
117 | Christensen, CB, Mikkelsen, BE, Toft, et al. The effect of introducing a free breakfast club on eating habits among students at vocational schools. BMC Public Health. 2019. 19:369. doi:10.1186/s12889-019-6701-9. | Intervention/Exposure; Outcome
118 | Christoph, MJ, Larson, NI, Winkler, et al. Longitudinal trajectories and prevalence of meeting dietary guidelines during the transition from adolescence to young adulthood. Am J Clin Nutr. 2019. 109:656-664. doi:10.1093/ajcn/nqy333. | Intervention/Exposure
119 | Chui JM, Lacy KE, Zheng MJ, Leech RM, McNaughton SA, Spence AC. Frequency and distribution of dietary energy, vegetable, fruit and discretionary food intakes in 18-month-old Australian children. Br J Nutr. 2023;130(3):513-524. doi:10.1017/S0007114522003324 | Study design; Intervention/Exposure
120 | Chung, S, Popkin, BM, Domino, et al. Effect of retirement on eating out and weight change: an analysis of gender differences. Obesity (Silver Spring). 2007. 15:1053-60. doi:10.1038/oby.2007.538. | Intervention/Exposure
121 | Cienfuegos, S, Gabel, K, Kalam, et al. Changes in body weight and metabolic risk during time restricted feeding in premenopausal versus postmenopausal women. Exp Gerontol. 2021. 154:111545. doi:10.1016/j.exger.2021.111545. | Intervention/Exposure
122 | Cienfuegos, S, Gabel, K, Kalam, et al. Effects of 4- and 6-h Time-Restricted Feeding on Weight and Cardiometabolic Health: A Randomized Controlled Trial in Adults with Obesity. Cell Metab. 2020. 32:366-378.e3. doi:10.1016/j.cmet.2020.06.018. | Intervention/Exposure
123 | Cienfuegos, S, Gabel, K, Kalam, et al. The effect of 4-h versus 6-h time restricted feeding on sleep quality, duration, insomnia severity and obstructive sleep apnea in adults with obesity. Nutr Health. 2022. 28:5-11. doi:10.1177/02601060211002347. | Intervention/Exposure
124 | Cipolla, C, Curatola, A, Ferretti, et al. Eating habits and lifestyle in children with obesity during the COVID19 lockdown: a survey in an Italian center. Acta Biomed. 2021. 92:e2021196. doi:10.23750/abm.v92i2.10912. | Study design
125 | Clark, DO, Keith, NR, Ofner, et al. Environments and situations as correlates of eating and drinking among women living with obesity and urban poverty. Obes Sci Pract. 2022. 8:153-163. doi:10.1002/osp4.557. | Study design
126 | Clayton, DJ, Stensel, DJ, James, et al. Effect of breakfast omission on subjective appetite, metabolism, acylated ghrelin and GLP-17-36 during rest and exercise. Nutrition. 2016. 32:179-85. doi:10.1016/j.nut.2015.06.013. | Outcome
127 | Cohen, DA, Ghosh-Dastidar, B, Conway, et al. Energy balance in adolescent girls: the trial of activity for adolescent girls cohort. Obesity (Silver Spring). 2014. 22:772-80. doi:10.1002/oby.20536. | Intervention/Exposure
128 | Colles, SL, Dixon, JB, O’Brien, et al. Night eating syndrome and nocturnal snacking: association with obesity, binge eating and psychological distress. Int J Obes (Lond). 2007. 31:1722-30. doi:10.1038/sj.ijo.0803664. | Study design; Intervention/Exposure
129 | Collings, PJ, Kelly, B, West, et al. Associations of TV Viewing Duration, Meals and Snacks Eaten When Watching TV, and a TV in the Bedroom with Child Adiposity. Obesity (Silver Spring). 2018. 26:1619-1628. doi:10.1002/oby.22288. | Study design; Intervention/Exposure
130 | Corbalán-Tutau MD, Madrid JA, Garaulet M. Timing and duration of sleep and meals in obese and normal weight women. Association with increase blood pressure. Appetite. 2012;59(1):9-16. doi:10.1016/j.appet.2012.03.015 | Intervention/Exposure
131 | Correia, JM, Santos, I, Pezarat-Correia, et al. Effects of Time-Restricted Feeding on Supramaximal Exercise Performance and Body Composition: A Randomized and Counterbalanced Crossover Study in Healthy Men. Int J Environ Res Public Health. 2021. 18:. doi:10.3390/ijerph18147227. | Intervention/Exposure
132 | Correia, JM, Santos, PDG, Pezarat-Correia, et al. Effect of Time-Restricted Eating and Resistance Training on High-Speed Strength and Body Composition. Nutrients. 2023. 15:. doi:10.3390/nu15020285. | Intervention/Exposure
133 | Crepinsek, MK, Singh, A, Bernstein, et al. Dietary effects of universal-free school breakfast: findings from the evaluation of the school breakfast program pilot project. J Am Diet Assoc. 2006. 106:1796-803. doi:10.1016/j.jada.2006.08.013. | Intervention/Exposure
134 | Crimarco, A, Turner-McGrievy, GM, Wirth, et al. The effects of meal-timing on self-rated hunger and dietary inflammatory potential among a sample of college students. J Am Coll Health. 2019. 67:328-337. doi:10.1080/07448481.2018.1481074. | Intervention/Exposure; Comparator
135 | Crose, A, Alvear, A, Singroy, et al. Time-Restricted Eating Improves Quality of Life Measures in Overweight Humans. Nutrients. 2021. 13:. doi:10.3390/nu13051430. | Intervention/Exposure
136 | Culnan, E, Reid, KJ, Zee, et al. Meal timing relative to DLMO: Associations with BMI and body fat. Sleep Health. 2021. 7:339-344. doi:10.1016/j.sleh.2021.01.001. | Intervention/Exposure
137 | Currenti, W, Buscemi, S, Cincione, et al. Time-Restricted Feeding and Metabolic Outcomes in a Cohort of Italian Adults. Nutrients. 2021. 13:. doi:10.3390/nu13051651. | Intervention/Exposure
138 | Cutler, GJ, Flood, A, Hannan, et al. Multiple sociodemographic and socioenvironmental characteristics are correlated with major patterns of dietary intake in adolescents. J Am Diet Assoc. 2011. 111:230-40. doi:10.1016/j.jada.2010.10.052. | Intervention/Exposure; Outcome
139 | Daly, P. Obese adolescent females and actual behavioral responses to a mindful eating intervention. Dissertation/thesis. 2013. 143p. | Study design; Publication status
140 | Daniel MM, Liboredo JC, Anastácio LR, et al. Incidence and Associated Factors of Weight Gain During the Covid-19 Pandemic. Front Nutr. 2022;9:818632. Published 2022 Feb 24. doi:10.3389/fnut.2022.818632 | Study design
141 | Daniels, SR. Breakfast is important. J Pediatr. 2012. 161:A1. doi:10.1016/j.jpeds.2012.09.029. | Study design
142 | Dashti, HassanS, Merino, Jordi, Lane, et al. Genome-wide association study of breakfast skipping links clock regulation with food timing. Am J Clin Nutr. 2019. 110:473-484. doi:10.1093/ajcn/nqz076. | Study design
143 | Dashti HS, Gómez-Abellán P, Qian J, et al. Late eating is associated with cardiometabolic risk traits, obesogenic behaviors, and impaired weight loss. Am J Clin Nutr. 2021;113(1):154-161. doi:10.1093/ajcn/nqaa264. | Intervention/Exposure; Comparator
144 | Davis, J, Shriver, L, Taylor, et al. Frequency of Eating Occasions and Relation to Weight Status in Children 2-5 Years of Age. J Acad Nutr Diet. 2016. 116:A52-A52. doi:10.1016/j.jand.2016.06.176. | Publication status
145 | de Castro, JM. The time of day of food intake influences overall intake in humans. J Nutr. 2004. 134:104-11. doi:10.1093/jn/134.1.104. | Intervention/Exposure
146 | de Oliveira Maranhão Pureza IR, da Silva Junior AE, Silva Praxedes DR, et al. Effects of time-restricted feeding on body weight, body composition and vital signs in low-income women with obesity: A 12-month randomized clinical trial. Clin Nutr. 2021;40(3):759-766. doi:10.1016/j.clnu.2020.06.036 | Intervention/Exposure
147 | de Oliveira Santos, R, Fisberg, RM, Marchioni, et al. Dietary patterns for meals of Brazilian adults. Br J Nutr. 2015. 114:822-8. doi:10.1017/s0007114515002445. | Study design; Intervention/Exposure; Outcome
148 | de Silva-Sanigorski, AM, Bell, AC, Kremer, et al. Reducing obesity in early childhood: results from Romp & Chomp, an Australian community-wide intervention program. Am J Clin Nutr. 2010. 91:831-40. doi:10.3945/ajcn.2009.28826. | Intervention/Exposure
149 | Deforche, B, Van Dyck, D, Deliens, et al. Changes in weight, physical activity, sedentary behaviour and dietary intake during the transition to higher education: a prospective study. Int J Behav Nutr Phys Act. 2015. 12:16. doi:10.1186/s12966-015-0173-9. | Intervention/Exposure
150 | Deliens, T, Clarys, P, Van Hecke, et al. Changes in weight and body composition during the first semester at university. A prospective explanatory study. Appetite. 2013. 65:111-6. doi:10.1016/j.appet.2013.01.024. | Intervention/Exposure
151 | Deschasaux-Tanguy M, Druesne-Pecollo N, Esseddik Y, et al. Diet and physical activity during the coronavirus disease 2019 (COVID-19) lockdown (March-May 2020): results from the French NutriNet-Santé cohort study. Am J Clin Nutr. 2021;113(4):924-938. doi:10.1093/ajcn/nqaa336 | Intervention/Exposure
152 | Deying, Liu, Yan, Huang, Chensihan, et al. Calorie Restriction with or without Time-Restricted Eating in Weight Loss. N Engl J Med. 2022. 386:1495-1504. doi:10.1056/NEJMoa2114833. | Intervention/Exposure
153 | Dicken, SJ, Mitchell, JJ, Newberry Le Vay, et al. Impact of the COVID-19 Pandemic on Diet Behaviour Among UK Adults: A Longitudinal Analysis of the HEBECO Study. Front Nutr. 2021. 8:788043. doi:10.3389/fnut.2021.788043. | Intervention/Exposure; Outcome
154 | Domaszewski, P, Konieczny, M, Dybek, et al. Comparison of the effects of six-week timerestricted eating on weight loss, body composition, and visceral fat in overweight older men and women. Exp Gerontol. 2023. 174:112116. doi:10.1016/j.exger.2023.112116. | Intervention/Exposure
155 | Domaszewski, P, Konieczny, M, Pakosz, et al. Effect of a six-week times restricted eating intervention on the body composition in early elderly men with overweight. Sci Rep. 2022. 12:9816. doi:10.1038/s41598-022-13904-9. | Intervention/Exposure
156 | Dong, F, Howard, AG, Herring, et al. Longitudinal associations of away-from-home eating, snacking, screen time, and physical activity behaviors with cardiometabolic risk factors among Chinese children and their parents. Am J Clin Nutr. 2017. 106:168-178. doi:10.3945/ajcn.116.146217. | Intervention/Exposure
157 | Dougkas, A, Minihane, AM, Givens, et al. Differential effects of dairy snacks on appetite, but not overall energy intake. Br J Nutr. 2012. 108:2274-85. doi:10.1017/s0007114512000323. | Intervention/Exposure
158 | Douglas, SM, Byers, AW, Leidy, et al. Habitual Breakfast Patterns Do Not Influence Appetite and Satiety Responses in Normal vs. High-Protein Breakfasts in Overweight Adolescent Girls. Nutrients. 2019. 11:. doi:10.3390/nu11061223. | Intervention/Exposure
159 | Duan, D, Pilla, SJ, Michalski, et al. Eating breakfast is associated with weight loss during an intensive lifestyle intervention for overweight/obesity. Obesity (Silver Spring). 2022. 30:378-388. doi:10.1002/oby.23340. | Health status
160 | Dubois L, Bédard B, Goulet D, Prud’homme D, Tremblay RE, Boivin M. Eating behaviors, dietary patterns and weight status in emerging adulthood and longitudinal associations with eating behaviors in early childhood. Int J Behav Nutr Phys Act. 2022;19(1):139. Published 2022 Nov 16. doi:10.1186/s12966-022-01376-z | Intervention/Exposure
161 | Dubois, L, Farmer, A, Girard, et al. Social factors and television use during meals and snacks is associated with higher BMI among pre-school children. Public Health Nutr. 2008. 11:1267-79. doi:10.1017/s1368980008002887. | Intervention/Exposure
162 | Dubois, L, Girard, M, Kent, et al. Breakfast eating and overweight in a pre-school population: Is there a link?. Public Health Nutr. 2006. 9:436-442. doi:10.1079/PHN2005867. | Study design
163 | Ducrot P, Méjean C, Bellisle F, Allès B, Hercberg S, Péneau S. Adherence to the French Eating Model is inversely associated with overweight and obesity: results from a large sample of French adults. Br J Nutr. 2018;120(2):231-239. doi:10.1017/S0007114518000909 | Study design
164 | Duffey, KJ, Gordon-Larsen, P, Jacobs, et al. Differential associations of fast food and restaurant food consumption with 3-y change in body mass index: the Coronary Artery Risk Development in Young Adults Study. Am J Clin Nutr. 2007. 85:201-8. doi:10.1093/ajcn/85.1.201. | Intervention/Exposure
165 | Durão C, Severo M, Oliveira A, et al. Association between dietary patterns and adiposity from 4 to 7 years of age. Public Health Nutr. 2017;20(11):1973-1982. doi:10.1017/S1368980017000854. | Intervention/Exposure
166 | Durão C, Severo M, Oliveira A, Lopes C. Sex-Heterogeneity on the Association between Dietary Patterns at 4 Years of Age with Adiposity and Cardiometabolic Risk Factors at 10 Years of Age. Nutrients. 2022;14(3):540. Published 2022 Jan 26. doi:10.3390/nu14030540 | Intervention/Exposure
167 | Duval, K, Strychar, I, Cyr, et al. Physical activity is a confounding factor of the relation between eating frequency and body composition. Am J Clin Nutr. 2008. 88:1200-5. doi:10.3945/ajcn.2008.26220. | Study design
168 | Eagle, TF, Gurm, R, Goldberg, et al. Health status and behavior among middle-school children in a midwest community: what are the underpinnings of childhood obesity?. Am Heart J. 2010. 160:1185-9. doi:10.1016/j.ahj.2010.09.019. | Study design; Intervention/Exposure
169 | Elimam, A, Marcus, C. Meal timing, fasting and glucocorticoids interplay in serum leptin concentrations and diurnal profile. Eur J Endocrinol. 2002. 147:181-8. doi:10.1530/eje.0.1470181. | Intervention/Exposure; Outcome
170 | Elinder, LS, Heinemans, N, Zeebari, et al. Longitudinal changes in health behaviours and body weight among Swedish school children-associations with age, gender and parental education-the SCIP school cohort. BMC Public Health. 2014. 14:640. doi:10.1186/1471-2458-14-640. | Outcome
171 | Elseifi, OS, Abdelrahman, DM, Mortada, et al. Effect of a nutritional education intervention on breakfast consumption among preparatory school students in Egypt. Int J Public Health. 2020. 65:893-903. doi:10.1007/s00038-020-01439-7. | Study design; Intervention/Exposure
172 | Embling R, Price MJ, Lee MD, Jones A, Wilkinson LL. Associations between dietary variety, portion size and body weight: prospective evidence from UK Biobank participants. Br J Nutr. 2023;130(7):1267-1277. doi:10.1017/S0007114523000156 | Intervention/Exposure
173 | Englund-Ögge L, Birgisdottir BE, Sengpiel V, et al. Meal frequency patterns and glycemic properties of maternal diet in relation to preterm delivery: Results from a large prospective cohort study. PLoS One. 2017;12(3):e0172896. Published 2017 Mar 1. doi:10.1371/journal.pone.0172896 | Outcome
174 | Eom, H, Lee, D, Cho, et al. The association between meal regularity and weight loss among women in commercial weight loss programs. Nutr Res Pract. 2022. 16:205-216. doi:10.4162/nrp.2022.16.2.205. | Intervention/Exposure
175 | Epel, E, Jimenez, S, Brownell, et al. Are stress eaters at risk for the metabolic syndrome?. Ann N Y Acad Sci. 2004. 1032:208-10. doi:10.1196/annals.1314.022. | Intervention/Exposure
176 | Erdem NZ, Bayraktaroğlu E, Samancı RA, Geçgil-Demir E, Tarakçı NG, Mert-Biberoğlu F. The effect of intermittent fasting diets on body weight and composition. Clin Nutr ESPEN. 2022;51:207-214. doi:10.1016/j.clnesp.2022.08.030 | Intervention/Exposure
177 | Estabrooks, PA, Shoup, JA, Gattshall, et al. Automated telephone counseling for parents of overweight children: a randomized controlled trial. Am J Prev Med. 2009. 36:35-42. doi:10.1016/j.amepre.2008.09.024. | Intervention/Exposure
178 | Fagundes, GBP, Tibaes, JRB, Silva, et al. Metabolic and behavioral effects of time-restricted eating in women with overweight or obesity: preliminary findings from a randomized study. Nutrition. 2023. 107:. doi:10.1016/j.nut.2022.111909. | Intervention/Exposure
179 | Fairclough, SJ, Hackett, AF, Davies, et al. Promoting healthy weight in primary school children through physical activity and nutrition education: a pragmatic evaluation of the CHANGE! randomised intervention study. BMC Public Health. 2013. 13:626. doi:10.1186/1471-2458-13-626. | Intervention/Exposure
180 | Fanelli, S, Walls, C, Taylor, et al. Skipping breakfast is associated with nutrient gaps and poorer diet quality among adults in the United States. Proc Nutr Soc. 2021. 80:1-1. doi:10.1017/S0029665121000495. | Study design; Publication status
181 | Farajian, P, Risvas, G, Karasouli, et al. Very high childhood obesity prevalence and low adherence rates to the Mediterranean diet in Greek children: the GRECO study. Atherosclerosis. 2011. 217:525-30. doi:10.1016/j.atherosclerosis.2011.04.003. | Study design
182 | Farshchi, HR, Taylor, MA, Macdonald, et al. Beneficial metabolic effects of regular meal frequency on dietary thermogenesis, insulin sensitivity, and fasting lipid profiles in healthy obese women. Am J Clin Nutr. 2005. 81:16-24. doi:10.1093/ajcn/81.1.16. | Comparator
183 | Farshchi, HR, Taylor, MA, Macdonald, et al. Regular meal frequency creates more appropriate insulin sensitivity and lipid profiles compared with irregular meal frequency in healthy lean women. Eur J Clin Nutr. 2004. 58:1071-7. doi:10.1038/sj.ejcn.1601935. | Comparator
184 | Fearnbach, N, Staiano, AE, Johannsen, et al. Predictors of Post-Exercise Energy Intake in Adolescents Ranging in Weight Status from Overweight to Severe Obesity. Nutrients. 2022. 14:. doi:10.3390/nu14010223. | Intervention/Exposure
185 | Feeley, AB, Musenge, E, Pettifor, et al. Investigation into longitudinal dietary behaviours and household socio-economic indicators and their association with BMI Z-score and fat mass in South African adolescents: the Birth to Twenty (Bt20) cohort. Public Health Nutr. 2013. 16:693-703. doi:10.1017/s1368980012003308. | Country
186 | Ferrocino, I, Pellegrini, M, D’Eusebio, et al. The Effects of Time-Restricted Eating on Metabolism and Gut Microbiota: A Real-Life Study. Nutrients. 2022. 14:. doi:10.3390/nu14132569. | Intervention/Exposure
187 | Field, AE, Austin, SB, Gillman, et al. Snack food intake does not predict weight change among children and adolescents. Int J Obes Relat Metab Disord. 2004. 28:1210-6. doi:10.1038/sj.ijo.0802762. | Intervention/Exposure
188 | Field, AE, Austin, SB, Taylor, et al. Relation between dieting and weight change among preadolescents and adolescents. Pediatrics. 2003. 112:900-6. doi:10.1542/peds.112.4.900. | Intervention/Exposure
189 | Fisher, Jennifer Orlet, Polonsky, H, Bauer, et al. Increasing Breakfast Consumption and Decreasing Childhood Obesity in Low-Income, Ethnically Diverse Youth. J Nutr Educ Behav. 2015. 47:S99-S99. doi:10.1016/j.jneb.2015.04.266. | Study design; Publication status
190 | Flanagan, A, Lowson, E, Griffin, et al. Effects of Maternal Nightshift Work on Evening Energy Intake, Diet Quality and Meal Timing in the Family: An Observational Study. Nurs Rep. 2021. 11:823-831. doi:10.3390/nursrep11040077. | Intervention/Exposure
191 | Fleischer, JG, Das, SK, Bhapkar, et al. Associations between the timing of eating and weight-loss in calorically restricted healthy adults: Findings from the CALERIE study. Exp Gerontol. 2022. 165:111837. doi:10.1016/j.exger.2022.111837. | Intervention/Exposure
192 | Flores, G, Lin, H. Factors predicting severe childhood obesity in kindergarteners. Int J Obes (Lond). 2013. 37:31-9. doi:10.1038/ijo.2012.168. | Intervention/Exposure
193 | Fogel, A, Goh, AT, Fries, et al. A description of an ‘obesogenic’ eating style that promotes higher energy intake and is associated with greater adiposity in 4.5year-old children: Results from the GUSTO cohort. Physiol Behav. 2017. 176:107-116. doi:10.1016/j.physbeh.2017.02.013. | Intervention/Exposure
194 | Fogteloo, AJ, Pijl, H, Roelfsema, et al. Impact of meal timing and frequency on the twenty-four-hour leptin rhythm. Horm Res. 2004. 62:71-8. doi:10.1159/000079326. | Outcome
195 | Ford, MC, Gordon, NP, Howell, et al. Obesity Severity, Dietary Behaviors, and Lifestyle Risks Vary by Race/Ethnicity and Age in a Northern California Cohort of Children with Obesity. J Obes. 2016. 2016:4287976. doi:10.1155/2016/4287976. | Study design
196 | Ford, Steve. Skipping breakfast ‘does not lead to overeating later in day’. Nurs Times. 2017: 168-168. | Study design
197 | Forde, CG, Fogel, A, McCrickerd, et al. Children’s Eating Behaviors and Energy Intake: Overlapping Influences and Opportunities for Intervention. Nestle Nutr Inst Workshop Ser. 2019. 91:55-67. doi:10.1159/000493695. | Study design; Intervention/Exposure
198 | Forkert, ECO, Moraes, ACF, Carvalho, et al. Skipping breakfast is associated with adiposity markers especially when sleep time is adequate in adolescents. Sci Rep. 2019. 9:6380. doi:10.1038/s41598-019-42859-7. | Study design
199 | Fortes Lde, S, Almeida Sde, S, Cipriani, et al. Inappropriate eating behavior: a longitudinal study with female adolescents. Rev Paul Pediatr. 2014. 32:85-91. doi:10.1590/s010305822014000100014. | Intervention/Exposure
200 | França ÉB, Mendes KG, Theodoro H, Olinto MTA, Canuto R. Association of dietary patterns, number of daily meals and anthropometric measures in women in age of menopause. Arch Endocrinol Metab. 2021;65(6):778-786. doi:10.20945/2359-3997000000414 | Study design
201 | Francis, LA, Rollins, BY, Bryce, et al. Biobehavioral Dysregulation and its Association with Obesity and Severe Obesity Trajectories from 2 to 15 Years of Age: A Longitudinal Study. Obesity (Silver Spring). 2020. 28:830-839. doi:10.1002/oby.22762. | Intervention/Exposure
202 | Freak-Poli, RL, Wolfe, R, Walls, et al. Participant characteristics associated with greater reductions in waist circumference during a four-month, pedometer-based, workplace health program. BMC Public Health. 2011. 11:824. doi:10.1186/1471-2458-11-824. | Study design; Intervention/Exposure
203 | French, SA, Mitchell, NR, Wolfson, et al. Portion size effects on weight gain in a free living setting. Obesity (Silver Spring). 2014. 22:1400-5. doi:10.1002/oby.20720. | Intervention/Exposure
204 | Fuglestad, PT, Jeffery, RW, Sherwood, et al. Lifestyle patterns associated with diet, physical activity, body mass index and amount of recent weight loss in a sample of successful weight losers. Int J Behav Nutr Phys Act. 2012. 9:79. doi:10.1186/1479-5868-9-79. | Study design
205 | Fujiwara, T, Nakata, R. Skipping breakfast is associated with reproductive dysfunction in post-adolescent female college students. Appetite. 2010. 55:714-7. doi:10.1016/j.appet.2010.08.005. | Study design; Intervention/Exposure; Outcome
206 | Fulkerson, JA, Friend, S, Flattum, et al. Promoting healthful family meals to prevent obesity: HOME Plus, a randomized controlled trial. Int J Behav Nutr Phys Act. 2015. 12:154. doi:10.1186/s12966-015-0320-3. | Intervention/Exposure
207 | Fulkerson, JA, Friend, S, Horning, et al. Family Home Food Environment and NutritionRelated Parent and Child Personal and Behavioral Outcomes of the Healthy Home Offerings via the Mealtime Environment (HOME) Plus Program: A Randomized Controlled Trial. J Acad Nutr Diet. 2018. 118:240-251. doi:10.1016/j.jand.2017.04.006. | Intervention/Exposure
208 | Fulkerson, JA, Neumark-Sztainer, D, Hannan, et al. Family meal frequency and weight status among adolescents: cross-sectional and 5-year longitudinal associations. Obesity (Silver Spring). 2008. 16:2529-34. doi:10.1038/oby.2008.388. | Intervention/Exposure
209 | Fuller-Tyszkiewicz, M, Skouteris, H, Hardy, et al. The associations between TV viewing, food intake, and BMI. A prospective analysis of data from the Longitudinal Study of Australian Children. Appetite. 2012. 59:945-8. doi:10.1016/j.appet.2012.09.009. | Intervention/Exposure
210 | Güvenç A. Effects of ramadan fasting on body composition, aerobic performance and lactate, heart rate and perceptual responses in young soccer players. J Hum Kinet. 2011;29:79-91. doi:10.2478/v10078-011-0042-9 | Intervention/Exposure
211 | Gabel, K, Fitzgibbon, ML, Yazici, et al. The basis and design for time-restricted eating compared with daily calorie restriction for weight loss and colorectal cancer risk reduction trial (TRE-CRC trial). Obesity (Silver Spring). 2022. 30:2376–2385. doi:10.1002/oby.23579. | Intervention/Exposure
212 | Gabel, K, Hoddy, KK, Burgess, et al. Effect of 8-h time-restricted feeding on sleep quality and duration in adults with obesity. Appl Physiol Nutr Metab. 2019. 44:903-906. doi:10.1139/apnm-2019-0032. | Intervention/Exposure
213 | Gabel, K, Hoddy, KK, Varady, et al. Safety of 8-h time restricted feeding in adults with obesity. Appl Physiol Nutr Metab. 2019. 44:107-109. doi:10.1139/apnm-2018-0389. | Study design; Intervention/Exposure
214 | Gabel, Kelsey, Varady, KristaA. Feasibility of Time-Restricted Eating. Obesity (19307381). 2020. 28:860-860. doi:10.1002/oby.22785. | Study design; Intervention/Exposure
215 | Gable, S, Chang, Y, Krull, et al. Television watching and frequency of family meals are predictive of overweight onset and persistence in a national sample of school-aged children. J Am Diet Assoc. 2007. 107:53-61. doi:10.1016/j.jada.2006.10.010. | Intervention/Exposure
216 | Gaeini, Z, Malmir, H, Mirmiran, et al. Snack consumption patterns and their associations with risk of incident metabolic syndrome: Tehran lipid and glucose study. Nutr Metab. 2023. 20:. doi:10.1186/s12986-023-00745-0. | Intervention/Exposure
217 | Gage, R, Girling-Butcher, M, Joe, et al. The Frequency and Context of Snacking among Children: An Objective Analysis Using Wearable Cameras. Nutrients. 2020. 13:. doi:10.3390/nu13010103. | Study design; Outcome
218 | Galfo, M, Censi, L, D’Addezio, et al. Overweight/obesity and lifestyle factors among Italian adolescents: the ALIADO study. Minerva Pediatr (Torino). 2022. 74:251-258. doi:10.23736/s2724-5276.16.04708-3. | Study design
219 | Gallant, A, Lundgren, J, O’Loughlin, et al. Night-eating symptoms and 2-year weight change in parents enrolled in the QUALITY cohort. Int J Obes (Lond). 2015. 39:1161-5. doi:10.1038/ijo.2015.36. | Intervention/Exposure
220 | Gamsızkan Z, Önmez A, Sahip Karakaş T. Chronobiological evaluation and an intervention study on timing of food intake in the treatment of obesity. Int J Clin Pract. 2021;75(10):e14502. doi:10.1111/ijcp.14502 | Study design; Intervention/Exposure; Outcome
221 | Gao, Y, Tsintzas, K, Macdonald, et al. Effects of intermittent (5:2) or continuous energy restriction on basal and postprandial metabolism: a randomised study in normal-weight, young participants. Eur J Clin Nutr. 2022. 76:65-73. doi:10.1038/s41430-021-00909-2. | Intervention/Exposure
222 | Garaulet M, Gómez-Abellán P, Alburquerque-Béjar JJ, Lee YC, Ordovás JM, Scheer FA. Timing of food intake predicts weight loss effectiveness [published correction appears in Int J Obes (Lond). 2013 Apr;37(4):624]. Int J Obes (Lond). 2013;37(4):604-611. doi:10.1038/ijo.2012.229 | Intervention/Exposure; Comparator
223 | Garaulet M, Gómez-Abellán P. Timing of food intake and obesity: a novel association. Physiol Behav. 2014;134:44-50. doi:10.1016/j.physbeh.2014.01.001 | Study design; Intervention/Exposure
224 | Garaulet, M, Ortega, FB, Ruiz, et al. Short sleep duration is associated with increased obesity markers in European adolescents: effect of physical activity and dietary habits. The HELENA study. Int J Obes (Lond). 2011. 35:1308-17. doi:10.1038/ijo.2011.149. | Intervention/Exposure
225 | Garaulet, M, Vera, B, Bonnet-Rubio, et al. Lunch eating predicts weight-loss effectiveness in carriers of the common allele at PERILIPIN1: the ONTIME (Obesity, Nutrigenetics, Timing, Mediterranean) study. Am J Clin Nutr. 2016. 104:1160-1166. doi:10.3945/ajcn.116.134528. | Intervention/Exposure; Comparator
226 | Gates, Gail, Perera, T. Association between Breakfast Consumption and Nutritional Status in 9 to 13 Year Old Children. J Nutr Educ Behav. 2013. 45:S31-S31. doi:10.1016/j.jneb.2013.04.084. | Study design; Publication status
227 | Gavela-Pérez T, Parra-Rodríguez A, Vales-Villamarín C, et al. Relationship between eating habits, sleep patterns and physical activity and the degree of obesity in children and adolescents. Endocrinol Diabetes Nutr (Engl Ed). 2023;70 Suppl 3:10-17. doi:10.1016/j.endien.2023.08.001 | Study design
228 | Geliebter, A, Astbury, NM, Aviram-Friedman, et al. Skipping breakfast leads to weight loss but also elevated cholesterol compared with consuming daily breakfasts of oat porridge or frosted cornflakes in overweight individuals: a randomised controlled trial. J Nutr Sci. 2014. 3:e56. doi:10.1017/jns.2014.51. | Outcome; Duration
229 | George, GC, Hanss-Nuss, H, Milani, et al. Food choices of low-income women during pregnancy and postpartum. J Am Diet Assoc. 2005. 105:899-907. doi:10.1016/j.jada.2005.03.028. | Intervention/Exposure; Outcome
230 | Gilardini, L, Croci, M, Pasqualinotto, et al. Dietary Habits and Cardiometabolic Health in Obese Children. Obes Facts. 2015. 8:101-9. doi:10.1159/000381157. | Intervention/Exposure
231 | Gilhooly, CH, Das, SK, Golden, et al. Food cravings and energy regulation: the characteristics of craved foods and their relationship with eating behaviors and weight change during 6 months of dietary energy restriction. Int J Obes (Lond). 2007. 31:1849-58. doi:10.1038/sj.ijo.0803672. | Intervention/Exposure; Comparator
232 | Gladka, MM, Le Couteur, DG, Simpson, et al. Midnight snacks might shorten your life: lifespan and healthspan advantages of eating less and at the right time. Cardiovasc Res. 2023. 119:e108-e110. doi:10.1093/cvr/cvad018. | Study design
233 | Gluck, ME, Venti, CA, Salbe, et al. Nighttime eating: commonly observed and related to weight gain in an inpatient food intake study. Am J Clin Nutr. 2008. 88:900-5. doi:10.1093/ajcn/88.4.900. | Intervention/Exposure
234 | Godlin Jeneta, J, Preetha, . Effect of breakfast in body mass index among college going students. Journal of Pharmaceutical Sciences and Research. 2016. 8:545-551. | Study design; Country
235 | Goetz, AR, Jindal, I, Moreno, et al. The Role of Sleep and Eating Patterns in Adiposity Gain among Preschool-Aged Children. Am J Clin Nutr. 2022. 116:1334-42. doi:10.1093/ajcn/nqac197. | Intervention/Exposure
236 | Goetz, AR, Jindal, I, Moreno, et al. The roles of sleep and eating patterns in adiposity gain among preschool-aged children. Am J Clin Nutr. 2022. 116:1334-1342. doi:10.1093/ajcn/nqac197. | Intervention/Exposure; Duplicate
237 | Gong, Qing-Hai, Li, Si-Xuan, Wang, et al. Dinner-to-bed time is independently associated with overweight/obesity in Chinese school-aged children. Eating & Weight Disorders. 2021. 26:2657-2663. doi:10.1007/s40519-021-01129-0. | Study design; Intervention/Exposure
238 | Gontijo, CA, Balieiro, LCT, Teixeira, et al. Effects of timing of food intake on eating patterns, diet quality and weight gain during pregnancy. Br J Nutr. 2020. 123:922-933. doi:10.1017/S0007114519003398. | Intervention/Exposure
239 | Gontijo, CA, Balieiro, LCT, Teixeira, et al. Higher energy intake at night effects daily energy distribution and contributes to excessive weight gain during pregnancy. Nutrition. 2020. 74:110756. doi:10.1016/j.nut.2020.110756. | Intervention/Exposure; Comparator
240 | González-González A, Betancourt-Ocampo D, Tavel-Gelrud D, Martínez-Lanz P. Risk eating behaviors in male and female students: a longitudinal study. Eat Behav. 2014;15(2):252-254. doi:10.1016/j.eatbeh.2014.03.006 | Intervention/Exposure
241 | Gonzalez, JT, Richardson, JD, Chowdhury, et al. Molecular adaptations of adipose tissue to 6Â weeks of morning fasting vs. daily breakfast consumption in lean and obese adults. J Physiol. 2018. 596:609-622. doi:10.1113/jp275113. | Outcome
242 | Gorin, AA, Phelan, S, Wing, et al. Promoting long-term weight control: does dieting consistency matter?. Int J Obes Relat Metab Disord. 2004. 28:278-81. doi:10.1038/sj.ijo.0802550. | Intervention/Exposure
243 | Gow, ML, Baur, LA, Ho, et al. Can early weight loss, eating behaviors and socioeconomic factors predict successful weight loss at 12- and 24-months in adolescents with obesity and insulin resistance participating in a randomised controlled trial?. Int J Behav Nutr Phys Act. 2016. 13:43. doi:10.1186/s12966-016-0367-9. | Intervention/Exposure
244 | Goyal, R, Julka, S. Impact of breakfast skipping on the health status of the population. Indian J Endocrinol Metab. 2014. 18:683-7. doi:10.4103/2230-8210.139233. | Study design; Country
245 | Grant, CL, Coates, AM, Dorrian, et al. Timing of food intake during simulated night shift impacts glucose metabolism: A controlled study. Chronobiol Int. 2017. 34:1003-1013. doi:10.1080/07420528.2017.1335318. | Outcome
246 | Greene, LF, Malpede, CZ, Henson, et al. Weight maintenance 2 years after participation in a weight loss program promoting low-energy density foods. Obesity (Silver Spring). 2006. 14:1795-801. doi:10.1038/oby.2006.207. | Intervention/Exposure
247 | Greenhill, Claire. How effective is time-restricted eating for weight loss?. Nature Reviews Endocrinology. 2020. 16:677-677. doi:10.1038/s41574-020-00434-5. | Study design; Intervention/Exposure
248 | Gregori, D, Maffeis, C, Jahns, et al. Snacking and obesity: urgency of a definition to explore such a relationship. J Am Diet Assoc. 2007. 107:562-563. doi:10.1016/j.jada.2007.02.025. | Study design; Publication status
249 | Grimes, M, Kuczmarski, MF, Bodt, et al. Breakfast Habits and Diet Quality in Economically Diverse African American and White Adults. Top Clin Nutr. 2018. 33:237-246. doi:10.1097/TIN.0000000000000147. | Study design
250 | Grydeland, May, Bergh, IngunnH, Bjelland, et al. Correlates of weight status among Norwegian 11-year-olds: The HEIA study. BMC Public Health. 2012. 12:1053-1053. doi:10.1186/1471-2458-12-1053. | Study design
251 | Gu, C, Brereton, N, Schweitzer, et al. Metabolic Effects of Late Dinner in Healthy Volunteers-A Randomized Crossover Clinical Trial. J Clin Endocrinol Metab. 2020. 105:2789–2802. doi:10.1210/clinem/dgaa354. | Intervention/Exposure; Comparator
252 | Gubbels, JS, Kremers, SPJ, Stafleu, et al. Clustering of energy balance-related behaviors in 5-year-old children: Lifestyle patterns and their longitudinal association with weight status development in early childhood. International Journal of Behavioral Nutrition and Physical Activity. 2012. 9:. doi:10.1186/1479-5868-9-77. | Intervention/Exposure
253 | Gupta, CC, Centofanti, S, Dorrian, et al. Subjective Hunger, Gastric Upset, and Sleepiness in Response to Altered Meal Timing during Simulated Shiftwork. Nutrients. 2019. 11:. doi:10.3390/nu11061352. | Intervention/Exposure; Outcome
254 | Gur, EB, Turan, GA, Ince, et al. Effect of Ramadan fasting on metabolic markers, dietary intake and abdominal fat distribution in pregnancy. Hippokratia. 2015. 19:298-303. | Intervention/Exposure
255 | Gustafson, CR, Rakhmatullaeva, N, Beckford, et al. Exercise and the timing of snack choice: Healthy snack choice is reduced in the post-exercise state. Nutrients. 2018. 10:. doi:10.3390/nu10121941. | Intervention/Exposure; Comparator
256 | Ha, AW, Kim, JH, Shin, et al. Eating habits, obesity related behaviors, and effects of Danhak exercise in elderly Koreans. Nutr Res Pract. 2010. 4:295-302. doi:10.4162/nrp.2010.4.4.295. | Intervention/Exposure
257 | Haganes KL, Silva CP, Eyjólfsdóttir SK, et al. Time-restricted eating and exercise training improve HbA1c and body composition in women with overweight/obesity: A randomized controlled trial. Cell Metab. 2022;34(10):1457-1471.e4. doi:10.1016/j.cmet.2022.09.003 | Intervention/Exposure
258 | Hajna, S, Leblanc, PJ, Faught, et al. Associations between family eating behaviours and body composition measures in peri-adolescents: results from a community-based study of school-aged children. Can J Public Health. 2014. 105:e15-21. doi:10.17269/cjph.105.4150. | Intervention/Exposure
259 | Halkjaer J, Tjønneland A, Overvad K, Sørensen TI. Dietary predictors of 5-year changes in waist circumference. J Am Diet Assoc. 2009;109(8):1356-1366. doi:10.1016/j.jada.2009.05.015 | Intervention/Exposure
260 | Harder-Lauridsen, NM, Rosenberg, A, Benatti, et al. Ramadan model of intermittent fasting for 28Â d had no major effect on body composition, glucose metabolism, or cognitive functions in healthy lean men. Nutrition. 2017. 37:92-103. doi:10.1016/j.nut.2016.12.015. | Intervention/Exposure
261 | Harding, S, Teyhan, A, Maynard, et al. Ethnic differences in overweight and obesity in early adolescence in the MRC DASH study: the role of adolescent and parental lifestyle. Int J Epidemiol. 2008. 37:162-72. doi:10.1093/ije/dym252. | Study design
262 | Hart, CN, Jelalian, E, Raynor, et al. Early patterns of food intake in an adolescent weight loss trial as predictors of BMI change. Eat Behav. 2010. 11:217-22. doi:10.1016/j.eatbeh.2010.05.001. | Intervention/Exposure
263 | Hartman, TJ, Masters, M, Flanders, et al. Self-Reported Eating-Occasion Frequency and Timing are Reproducible and Relatively Valid in the American Cancer Society Cancer Prevention Study-3 Diet Assessment Substudy. J Nutr. 2023. 152:2827-2836. doi:10.1093/jn/nxac206. | Study design; Outcome
264 | Hassan, BK, Cunha, DB, da Veiga, et al. Changes in breakfast frequency and composition during adolescence: The Adolescent Nutritional Assessment Longitudinal Study, a cohort from Brazil. PLoS One. 2018. 13:e0200587. doi:10.1371/journal.pone.0200587. | Outcome
265 | Hatanaka, M, Hatamoto, Y, Tajiri, et al. An Earlier First Meal Timing Associate with Weight Loss Effectiveness in A 12-Week Weight Loss Support Program. Nutrients. 2022. 14:. doi:10.3390/nu14020249. | Intervention/Exposure
266 | Hatanaka, M, Hatamoto, Y, Tajiri, et al. An Earlier First Meal Timing Associates with Weight Loss Effectiveness in A 12-Week Weight Loss Support Program. Nutrients. 2022. 14:. doi:10.3390/nu14020249. | Intervention/Exposure; Duplicate
267 | He, M, Wang, J, Liang, et al. Time-restricted eating with or without low-carbohydrate diet reduces visceral fat and improves metabolic syndrome: a randomized trial. Cell reports. Medicine. 2022. 3:100777. doi:10.1016/j.xcrm.2022.100777. | Intervention/Exposure
268 | Hebestreit A, Börnhorst C, Barba G, et al. Associations between energy intake, daily food intake and energy density of foods and BMI z-score in 2-9-year-old European children [published correction appears in Eur J Nutr. 2014 Aug;53(5);1297-8]. Eur J Nutr. 2014;53(2):673-681. doi:10.1007/s00394-013-0575-x | Study design; Intervention/Exposure
269 | Heden, TD, Liu, Y, Sims, et al. Meal frequency differentially alters postprandial triacylglycerol and insulin concentrations in obese women. Obesity (Silver Spring). 2013. 21:123-9. doi:10.1002/oby.20247. | Outcome
270 | Heden, Tim, Liu, Ying, Sims, et al. Influence of Meal Frequency on Postprandial Glycemia and Lipemia in Obese Individuals. Med Sci Sports Exerc. 2011. 43:673-673. doi:10.1249/01.MSS.0000401864.68675.ce. | Publication status
271 | Hermans, RC, Herman, CP, Larsen, et al. Social modeling effects on young women’s breakfast intake. J Am Diet Assoc. 2010. 110:1901-5. doi:10.1016/j.jada.2010.09.007. | Intervention/Exposure
272 | Hermenegildo Y, López-García E, García-Esquinas E, Pérez-Tasigchana RF, Rodríguez-Artalejo F, Guallar-Castillón P. Distribution of energy intake throughout the day and weight gain: a population-based cohort study in Spain [published correction appears in Br J Nutr. 2017 Mar;117(5):766. doi: 10.1017/S0007114516002385]. Br J Nutr. 2016;115(11):2003-2010. doi:10.1017/S0007114516000891 | Intervention/Exposure
273 | Hermenegildo-López Y, Donat-Vargas C, Sandoval-Insausti H, et al. A Higher Intake of Energy at Dinner Is Associated with Incident Metabolic Syndrome: A Prospective Cohort Study in Older Adults. Nutrients. 2021;13(9):3035. Published 2021 Aug 30. doi:10.3390/nu13093035 | Intervention/Exposure
274 | Hibi, M, Hari, S, Yamaguchi, et al. Effect of short-term increase in meal frequency on glucose metabolism in individuals with normal glucose tolerance or impaired fasting glucose: A randomized crossover clinical trial. Nutrients. 2019. 11:. doi:10.3390/nu11092126. | Outcome
275 | Hibi, M, Masumoto, A, Naito, et al. Nighttime snacking reduces whole body fat oxidation and increases LDL cholesterol in healthy young women. Am J Physiol Regul Integr Comp Physiol. 2013. 304:R94-r101. doi:10.1152/ajpregu.00115.2012. | Intervention/Exposure; Comparator
276 | Hoddy, KK, Kroeger, CM, Trepanowski, et al. Meal timing during alternate day fasting: Impact on body weight and cardiovascular disease risk in obese adults. Obesity (Silver Spring). 2014. 22:2524-31. doi:10.1002/oby.20909. | Intervention/Exposure; Duration
277 | Hoertel, HA, Will, MJ, Leidy, et al. A randomized crossover, pilot study examining the effects of a normal protein vs. high protein breakfast on food cravings and reward signals in overweight/obese “breakfast skipping", late-adolescent girls. Nutr J. 2014. 13:80. doi:10.1186/1475-2891-13-80. | Outcome
278 | Hohman, EE, Balantekin, KN, Birch, et al. Dieting is associated with reduced bone mineral accrual in a longitudinal cohort of girls. BMC Public Health. 2018. 18:1285. doi:10.1186/s12889-018-6206-y. | Intervention/Exposure; Outcome
279 | Holmbäck U, Lowden A, Akerfeldt T, et al. The human body may buffer small differences in meal size and timing during a 24-h wake period provided energy balance is maintained. J Nutr. 2003;133(9):2748-2755. doi:10.1093/jn/133.9.2748 | Outcome
280 | Holmstrup, ME, Owens, CM, Fairchild, et al. Effect of meal frequency on glucose and insulin excursions over the course of a day. e-SPEN. 2010. 5:e277-e280. doi:10.1016/j.eclnm.2010.10.001. | Outcome
281 | Hopkins, LC, Sattler, M, Steeves, et al. Breakfast Consumption Frequency and Its Relationships to Overall Diet Quality, Using Healthy Eating Index 2010, and Body Mass Index among Adolescents in a Low-Income Urban Setting. Ecol Food Nutr. 2017. 56:297-311. doi:10.1080/03670244.2017.1327855. | Study design
282 | Huang, SX, Fu, YX, Wang, et al. Effects of breakfast with different calorigenic amounts on blood glucose, insulin and glucagon levels. J Zhejiang Univ Sci. 2003. 4:753-5. doi:10.1631/jzus.2003.0753. | Outcome; Country
283 | Hunsberger M, Mehlig K, Börnhorst C, et al. Dietary Carbohydrate and Nocturnal Sleep Duration in Relation to Children’s BMI: Findings from the IDEFICS Study in Eight European Countries. Nutrients. 2015;7(12):10223-10236. Published 2015 Dec 8. doi:10.3390/nu7125529 | Study design
284 | Huseinovic, E, Winkvist, A, Bertz, et al. Changes in food choice during a successful weight loss trial in overweight and obese postpartum women. Obesity (Silver Spring). 2014. 22:2517-23. doi:10.1002/oby.20895. | Intervention/Exposure
285 | Hutchison, AT, Liu, B, Wood, et al. Effects of Intermittent Versus Continuous Energy Intakes on Insulin Sensitivity and Metabolic Risk in Women with Overweight. Obesity (Silver Spring). 2019. 27:50-58. doi:10.1002/oby.22345. | Intervention/Exposure
286 | Hutchison, AT, Regmi, P, Manoogian, et al. Time-Restricted Feeding Improves Glucose Tolerance in Men at Risk for Type 2 Diabetes: A Randomized Crossover Trial. Obesity (Silver Spring). 2019. 27:724-732. doi:10.1002/oby.22449. | Intervention/Exposure
287 | Huus, K, Brekke, HK, Ludvigsson, et al. Relationship of food frequencies as reported by parents to overweight and obesity at 5 years. Acta Paediatr. 2009. 98:139-43. doi:10.1111/j.1651-2227.2008.01043.x. | Intervention/Exposure
288 | Ibe, Y, Miyakawa, H, Fuse-Nagase, et al. Association of eating three meals irregularly with changes in BMI and weight among young Japanese men and women: A 2-year follow-up. Physiol Behav. 2016. 163:81-87. doi:10.1016/j.physbeh.2016.04.045. | Intervention/Exposure
289 | Ishimoto, Y, Yoshida, M, Nagata, et al. Consuming breakfast and exercising longer during high school increases bone mineral density in young adult men. J Bone Miner Metab. 2013. 31:329-36. doi:10.1007/s00774-012-0415-8. | Outcome
290 | Ishizuka R, Otaki N, Tai Y, et al. Breakfast Skipping and Declines in Cognitive Score Among Community-Dwelling Older Adults: A Longitudinal Study of the HEIJO-KYO Cohort. J Geriatr Psychiatry Neurol. 2023;36(4):316-322. doi:10.1177/08919887221135551 | Outcome
291 | Iwasaki, T, Hirose, A, Azuma, et al. Association between eating behavior and poor glycemic control in Japanese adults. Sci Rep. 2019. 9:3418. doi:10.1038/s41598-019-39001-y. | Outcome
292 | Jääskeläinen, A, Schwab, U, Kolehmainen, et al. Associations of meal frequency and breakfast with obesity and metabolic syndrome traits in adolescents of Northern Finland Birth Cohort 1986. Nutr Metab Cardiovasc Dis. 2013. 23:1002-9. doi:10.1016/j.numecd.2012.07.006 . | Study design
293 | Jääskeläinen, A, Schwab, U, Kolehmainen, et al. Meal frequencies modify the effect of common genetic variants on body mass index in adolescents of the northern Finland birth cohort 1986. PLoS One. 2013. 8:e73802. doi:10.1371/journal.pone.0073802. | Study design
294 | Jackson, SL, Cunningham, SA. The stability of children’s weight status over time, and the role of television, physical activity, and diet. Prev Med. 2017. 100:229-234. doi:10.1016/j.ypmed.2017.04.026. | Intervention/Exposure
295 | Jacob, R, Tremblay, A, Panahi, et al. Is the timing of food intake a potential indicator of low weight loss responders? A secondary analysis of three weight loss studies. Clin Obes. 2020. 10:e12360. doi:10.1111/cob.12360. | Intervention/Exposure
296 | Jacobson, IG, Smith, TC, Smith, et al. Disordered eating and weight changes after deployment: longitudinal assessment of a large US military cohort. Am J Epidemiol. 2009. 169:415-27. doi:10.1093/aje/kwn366. | Intervention/Exposure
297 | Jaeger, V, Koletzko, B, Luque, et al. Distribution of energy and macronutrient intakes across eating occasions in European children from 3 to 8Â years of age: The EU Childhood Obesity Project Study. Eur J Nutr. 2023. 62:165-174. doi:10.1007/s00394-022-02944-6. | Intervention/Exposure; Comparator
298 | Jaeger, V, Koletzko, B, Luque, et al. Eating Frequency in European Children from 1 to 96 Months of Age: Results of the Childhood Obesity Project Study. Nutrients. 2023. 15:. doi:10.3390/nu15040984. | Outcome
299 | Jaeger, V, Koletzko, B, Luque, et al. Time of Dietary Energy and Nutrient Intake and Body Mass Index in Children: Compositional Data Analysis from the Childhood Obesity Project (CHOP) Trial. Nutrients. 2022. 14:. doi:10.3390/nu14204356. | Intervention/Exposure; Comparator
300 | Jakubowicz, D, Barnea, M, Wainstein, et al. Effects of caloric intake timing on insulin resistance and hyperandrogenism in lean women with polycystic ovary syndrome. Clin Sci (Lond). 2013. 125:423-32. doi:10.1042/cs20130071. | Intervention/Exposure; Comparator
301 | Jakubowicz, D, Barnea, M, Wainstein, et al. High caloric intake at breakfast vs. dinner differentially influences weight loss of overweight and obese women. Obesity (Silver Spring). 2013. 21:2504-12. doi:10.1002/oby.20460. | Intervention/Exposure; Comparator
302 | Jakubowicz, D, Wainstein, J, Landau, et al. Influences of Breakfast on Clock Gene Expression and Postprandial Glycemia in Healthy Individuals and Individuals With Diabetes: a Randomized Clinical Trial. Diabetes Care. 2017. 40:1573–1579. doi:10.2337/dc16-2753. | Outcome
303 | Jamshed, Humaira, Steger, FeliciaL, Bryan, et al. Effectiveness of Early Time-Restricted Eating for Weight Loss, Fat Loss, and Cardiometabolic Health in Adults With Obesity: A Randomized Clinical Trial. JAMA Intern Med. 2022. 182:953-962. doi:10.1001/jamainternmed.2022.3050. | Intervention/Exposure
304 | Jansen, W, Mackenbach, JP, Joosten-van Zwanenburg, et al. Weight status, energy-balance behaviours and intentions in 9-12-year-old inner-city children. J Hum Nutr Diet. 2010. 23:85-96. doi:10.1111/j.1365-277X.2009.01027.x. | Study design
305 | Jeffery, RW, Abbott, G, Ball, et al. Behavior and weight correlates of weight-control efforts in Australian women living in disadvantage: The READI study. International Journal of Behavioral Nutrition and Physical Activity. 2013. 10:. doi:10.1186/1479-5868-10-52. | Intervention/Exposure
306 | Jeffery, RW, Rick, AM. Cross-sectional and longitudinal associations between body mass index and marriage-related factors. Obes Res. 2002. 10:809-15. doi:10.1038/oby.2002.109. | Intervention/Exposure
307 | Johnson, BA, Kremer, PJ, Swinburn, et al. Multilevel analysis of the Be Active Eat Well intervention: environmental and behavioural influences on reductions in child obesity risk. Int J Obes (Lond). 2012. 36:901-7. doi:10.1038/ijo.2012.23. | Intervention/Exposure
308 | Johnson, SS, Paiva, AL, Cummins, et al. Transtheoretical model-based multiple behavior intervention for weight management: effectiveness on a population basis. Prev Med. 2008. 46:238-46. doi:10.1016/j.ypmed.2007.09.010. | Intervention/Exposure
309 | Jones, Robert, Pabla, Pardeep, Mallinson, et al. Two weeks of early time-restricted feeding (eTRF) improves skeletal muscle insulin and anabolic sensitivity in healthy men. Am J Clin Nutr. 2020. 112:1015-1028. doi:10.1093/ajcn/nqaa192. | Intervention/Exposure
310 | Joseph, LS, Gorin, AA, Mobley, et al. Impact of a Short-Term Nutrition Education Child Care Pilot Intervention on Preschool Children’s Intention To Choose Healthy Snacks and Actual Snack Choices. Child Obes. 2015. 11:513-20. doi:10.1089/chi.2015.0028. | Intervention/Exposure
311 | Kahleova, H, Lloren, JI, Mashchak, et al. Meal Frequency and Timing Are Associated with Changes in Body Mass Index in Adventist Health Study 2. J Nutr. 2017. 147:1722-1728. doi:10.3945/jn.116.244749. | Study design
312 | Kalam, F, Akasheh, RT, Cienfuegos, et al. Effect of time-restricted eating on sex hormone levels in premenopausal and postmenopausal females. Obesity (Silver Spring). 2023. 31 Suppl 1:57-62. doi:10.1002/oby.23562. | Intervention/Exposure
313 | Kaneko, H, Itoh, H, Kiriyama, et al. Possible association between eating behaviors and cardiovascular disease in the general population: Analysis of a nationwide epidemiological database. Atherosclerosis. 2021. 320:79-85. doi:10.1016/j.atherosclerosis.2021.01.022. | Outcome
314 | Kapinos, KA, Yakusheva, O. Environmental influences on young adult weight gain: evidence from a natural experiment. J Adolesc Health. 2011. 48:52-8. doi:10.1016/j.jadohealth.2010.05.021. | Intervention/Exposure
315 | Karatzi, K, Georgiopoulos, G, Yannakoulia, et al. Eating frequency predicts new onset hypertension and the rate of progression of blood pressure, arterial stiffness, and wave reflections. J Hypertens. 2016. 34:429-37; discussion 437. doi:10.1097/hjh.0000000000000822 . | Outcome
316 | Karfopoulou, Eleni, Brikou, Dora, Mamalaki, et al. Dietary patterns in weight loss maintenance: results from the MedWeight study. Eur J Nutr. 2017. 56:991-1002. doi:10.1007/s00394-015-1147-z. | Study design
317 | Karras, SN, Koufakis, T, Adamidou, et al. Effects of Christian Orthodox Fasting Versus Time-Restricted Eating on Plasma Irisin Concentrations Among Overweight Metabolically Healthy Individuals. Nutrients. 2021. 13:. doi:10.3390/nu13041071. | Intervention/Exposure
318 | Karras, SN, Koufakis, T, Adamidou, et al. Effects of orthodox religious fasting versus combined energy and time restricted eating on body weight, lipid concentrations and glycaemic profile. Int J Food Sci Nutr. 2021. 72:82-92. doi:10.1080/09637486.2020.1760218. | Intervention/Exposure
319 | Karras, SN, Koufakis, T, Adamidou, et al. Implementation of Christian Orthodox fasting improves plasma adiponectin concentrations compared with time-restricted eating in overweight premenopausal women. Int J Food Sci Nutr. 2022. 73:210-220. doi:10.1080/09637486.2021.1941803. | Intervention/Exposure
320 | Karras, SN, Koufakis, T, Adamidou, et al. Similar late effects of a 7-week orthodox religious fasting and a time restricted eating pattern on anthropometric and metabolic profiles of overweight adults. Int J Food Sci Nutr. 2021. 72:248-258. doi:10.1080/09637486.2020.1787959 . | Intervention/Exposure
321 | Katsuura-Kamano, S, Arisawa, K, Uemura, et al. Association of skipping breakfast and short sleep duration with the prevalence of metabolic syndrome in the general Japanese population: Baseline data from the Japan Multi-Institutional Collaborative cohort study. Prev Med Rep. 2021. 24:101613. doi:10.1016/j.pmedr.2021.101613. | Study design
322 | Kawada, T, Okada, K, Amezawa, et al. Components of the metabolic syndrome and lifestyle factors in Japanese male workers. Metab Syndr Relat Disord. 2008. 6:263-6. doi:10.1089/met.2008.0020. | Study design
323 | Keogh, JB, Pedersen, E, Petersen, et al. Effects of intermittent compared to continuous energy restriction on short-term weight loss and long-term weight loss maintenance. Clin Obes. 2014. 4:150-6. doi:10.1111/cob.12052. | Intervention/Exposure
324 | Kerkadi, A, Sadig, AH, Bawadi, et al. The Relationship between Lifestyle Factors and Obesity Indices among Adolescents in Qatar. Int J Environ Res Public Health. 2019. 16:. doi:10.3390/ijerph16224428. | Study design
325 | Keski-Rahkonen A, Bulik CM, Pietiläinen KH, Rose RJ, Kaprio J, Rissanen A. Eating styles, overweight and obesity in young adult twins. Eur J Clin Nutr. 2007;61(7):822-829. doi:10.1038/sj.ejcn.1602601 | Study design
326 | Kesztyüs, D, Cermak, P, Gulich, et al. Adherence to Time-Restricted Feeding and Impact on Abdominal Obesity in Primary Care Patients: Results of a Pilot Study in a Pre-Post Design. Nutrients. 2019. 11:. doi:10.3390/nu11122854. | Study design; Intervention/Exposure
327 | Kesztyüs, D, Cermak, P, KesztyÃ¼s, et al. Early or Delayed Onset of Food Intake in TimeRestricted Eating: Associations with Markers of Obesity in a Secondary Analysis of Two Pilot Studies. Int J Environ Res Public Health. 2021. 18:. doi:10.3390/ijerph18189935. | Study design; Intervention/Exposure
328 | Kesztyüs D, Vorwieger E, Schönsteiner D, Gulich M, Kesztyüs T. Applicability of time-restricted eating for the prevention of lifestyle-dependent diseases in a working population: results of a pilot study in a pre-post design. Ger Med Sci. 2021;19:Doc04. Published 2021 Mar 29. doi:10.3205/000291 | Study design; Intervention/Exposure
329 | Kim, H, Yoon, E, Kim, et al. Short-term Effects of Eating Behavior Modification on Metabolic Syndrome-Related Risks in Overweight and Obese Korean Adults. J Obes Metab Syndr. 2022. 31:70-80. doi:10.7570/jomes21074. | Intervention/Exposure
330 | Kim, HS, Jung, SJ, Jang, et al. Rice-based breakfast improves fasting glucose and HOMA-IR in Korean adolescents who skip breakfast, but breakfast skipping increases aromatic amino acids associated with diabetes prediction in Korean adolescents who skip breakfast: a randomized, parallel-group, controlled trial. Nutr Res Pract. 2022. 16:450-463. doi:10.4162/nrp.2022.16.4.450. | Intervention/Exposure; Comparator
331 | Kim, J, Song, Y. Early Time-Restricted Eating Reduces Weight and Improves Glycemic Response in Young Adults: A Pre-Post Single-Arm Intervention Study. Obes Facts. 2023. 16:69-81. doi:10.1159/000527838. | Study design; Intervention/Exposure
332 | Kim, S, DeRoo, LA, Sandler, et al. Eating patterns and nutritional characteristics associated with sleep duration. Public Health Nutr. 2011. 14:889-95. doi:10.1017/s136898001000296x. | Study design; Outcome
333 | Kirk, TR. Role of dietary carbohydrate and frequent eating in body-weight control. Proc Nutr Soc. 2000. 59:349-358. doi:10.1017/s0029665100000409. | Study design
334 | Kirsten, Wilma. Breakfast. Positive Health. 2010. 1-1. | Study design
335 | Kishimoto, T, Churiki, M, Miyazato, et al. Association between lifestyle and metabolic syndrome incidence of workers in northern Okinawa, Japan: A cohort study. Preventive Medicine Reports. 2022. 30:. doi:10.1016/j.pmedr.2022.101995. | Outcome
336 | Klein, EG, Lytle, LA, Chen, et al. Social ecological predictors of the transition to overweight in youth: results from the Teens Eating for Energy and Nutrition at Schools (TEENS) study. J Am Diet Assoc. 2008. 108:1163-9. doi:10.1016/j.jada.2008.04.007. | Intervention/Exposure
337 | Klohe-Lehman, DM, Freeland-Graves, J, Clarke, et al. Low-income, overweight and obese mothers as agents of change to improve food choices, fat habits, and physical activity in their 1-to-3-year-old children. J Am Coll Nutr. 2007. 26:196-208. doi:10.1080/07315724.2007.10719602. | Intervention/Exposure
338 | Kobayashi, F, Ogata, H, Omi, et al. Effect of breakfast skipping on diurnal variation of energy metabolism and blood glucose. Obes Res Clin Pract. 2014. 8:e201-98. doi:10.1016/j.orcp.2013.01.001. | Comparator; Outcome
339 | Kohri, T, Shimizu, A, Suzuki, et al. Longitudinal Study on Relationships among Snack Energy Intake, Body Mass Index, and Nutrient Intake in Japanese Children Aged 6-7 Years. J Nutr Sci Vitaminol (Tokyo). 2021. 67:163-169. doi:10.3177/jnsv.67.163. | Intervention/Exposure
340 | Kong, A, Beresford, SA, Alfano, et al. Associations between snacking and weight loss and nutrient intake among postmenopausal overweight to obese women in a dietary weight-loss intervention. J Am Diet Assoc. 2011. 111:1898–1903. doi:10.1016/j.jada.2011.09.012. | Study design
341 | Kong, Angela, Beresford, ShirleyAA, Alfano, et al. Self-Monitoring and Eating-Related Behaviors Are Associated with 12-Month Weight Loss in Postmenopausal Overweight-toObese Women. J Acad Nutr Diet. 2012. 112:1428-1435. doi:10.1016/j.jand.2012.05.014. | Study design
342 | Koopman, KE, Caan, MW, Nederveen, et al. Hypercaloric diets with increased meal frequency, but not meal size, increase intrahepatic triglycerides: a randomized controlled trial. Hepatology. 2014. 60:545-53. doi:10.1002/hep.27149. | Comparator
343 | Kosti, RI, Panagiotakos, DB, Mihas, et al. Dietary habits, physical activity and prevalence of overweight/obesity among adolescents in Greece: the Vyronas study. Med Sci Monit. 2007. 13:Cr437-44. | Study design
344 | Kotarsky, CJ, Johnson, NR, Mahoney, et al. Time-restricted eating and concurrent exercise training reduces fat mass and increases lean mass in overweight and obese adults. Physiol Rep. 2021. 9:e14868. doi:10.14814/phy2.14868. | Intervention/Exposure
345 | Kuhlmann, KristinL. Weight change in college freshmen: Personal, interpersonal and situational influences. . 2013. p-202. | Study design; Publication status
346 | Lagarde, D, Kazak, L. The timing of eating controls energy use. Science (80- ). 2022. 378:251-252. doi:10.1126/science.ade6720. | Study design
347 | Lakkakula, AP, Zanovec, M, Silverman, et al. Black children with high preferences for fruits and vegetables are at less risk of being at risk of overweight or overweight. J Am Diet Assoc. 2008. 108:1912-5. doi:10.1016/j.jada.2008.08.019. | Study design; Intervention/Exposure
348 | Laramée, C, Drapeau, V, Valois, et al. Evaluation of a Theory-Based Intervention Aimed at Reducing Intention to Use Restrictive Dietary Behaviors Among Adolescent Female Athletes. J Nutr Educ Behav. 2017. 49:497-504.e1. doi:10.1016/j.jneb.2017.03.009. | Intervention/Exposure
349 | Larson, N, Fulkerson, J, Story, et al. Shared meals among young adults are associated with better diet quality and predicted by family meal patterns during adolescence. Public Health Nutr. 2013. 16:883-93. doi:10.1017/s1368980012003539. | Intervention/Exposure
350 | Larson, NI, Neumark-Sztainer, D, Hannan, et al. Family meals during adolescence are associated with higher diet quality and healthful meal patterns during young adulthood. J Am Diet Assoc. 2007. 107:1502-10. doi:10.1016/j.jada.2007.06.012. | Intervention/Exposure; Outcome
351 | Larson, NI, Neumark-Sztainer, D, Story, et al. Weight control behaviors and dietary intake among adolescents and young adults: longitudinal findings from Project EAT. J Am Diet Assoc. 2009. 109:1869-77. doi:10.1016/j.jada.2009.08.016. | Intervention/Exposure; Outcome
352 | Larson, Nicole, Miller, Jonathan, Watts, et al. What, When, and Where: Measures of Adolescent Snacking Behaviors Are Associated With Dietary Intake and Weight Status. J Adolesc Health. 2016. 58:S11-S12. doi:10.1016/j.jadohealth.2015.10.038. | Publication status
353 | Larson, Nicole, Qi, Wang, Berge, et al. Eating breakfast together as a family: mealtime experiences and associations with dietary intake among adolescents in rural Minnesota, USA. Public Health Nutr. 2016. 19:1565-1574. doi:10.1017/S1368980016000379. | Study design; Intervention/Exposure
354 | Laska, MN, Lytle, LA, Nanney, et al. Results of a 2-year randomized, controlled obesity prevention trial: Effects on diet, activity and sleep behaviors in an at-risk young adult population. Prev Med. 2016. 89:230-236. doi:10.1016/j.ypmed.2016.06.001. | Intervention/Exposure
355 | Laurson, K, Eisenmann, JC, Moore, et al. Lack of association between television viewing, soft drinks, physical activity and body mass index in children. Acta Paediatr. 2008. 97:795-800. doi:10.1111/j.1651-2227.2008.00713.x. | Intervention/Exposure
356 | LeCheminant, JD, Christenson, E, Bailey, et al. Restricting night-time eating reduces daily energy intake in healthy young men: a short-term cross-over study. Br J Nutr. 2013. 110:2108-13. doi:10.1017/s0007114513001359. | Intervention/Exposure
357 | LeCroy, MN, Truesdale, KP, Matheson, et al. Snacking characteristics and patterns and their associations with diet quality and BMI in the Childhood Obesity Prevention and Treatment Research Consortium. Public Health Nutr. 2019. 22:3189-3199. doi:10.1017/s1368980019000958. | Study design
358 | Lee, Insook, Bang, Kyung-Sook, Moon, et al. Risk Factors for Obesity Among Children Aged 24 to 80 months in Korea: A Decision Tree Analysis. J Pediatr Nurs. 2019. 46:e15-e23. doi:10.1016/j.pedn.2019.02.004. | Study design
359 | Leech, RM, McNaughton, SA, Crawford, et al. Family food involvement and frequency of family dinner meals among Australian children aged 10-12years. Cross-sectional and longitudinal associations with dietary patterns. Appetite. 2014. 75:64-70. doi:10.1016/j.appet.2013.12.021. | Intervention/Exposure
360 | Leidy, HJ, Armstrong, CL, Tang, et al. The influence of higher protein intake and greater eating frequency on appetite control in overweight and obese men. Obesity (Silver Spring). 2010. 18:1725-32. doi:10.1038/oby.2010.45. | Outcome
361 | Lemmens, SG, Martens, EA, Born, et al. Staggered meal consumption facilitates appetite control without affecting postprandial energy intake. J Nutr. 2011. 141:482-8. doi:10.3945/jn.110.133264. | Intervention/Exposure
362 | Leong, SL, Gray, A, Haszard, et al. Weight-Control Methods, 3-Year Weight Change, and Eating Behaviors: A Prospective Nationwide Study of Middle-Aged New Zealand Women. J Acad Nutr Diet. 2016. 116:1276-84. doi:10.1016/j.jand.2016.02.021. | Intervention/Exposure
363 | Leung, GKW, Davis, R, Huggins, et al. Does rearranging meal times at night improve cardiovascular risk factors? An Australian pilot randomised trial in night shift workers. Nutr Metab Cardiovasc Dis. 2021. 31:1890-1902. doi:10.1016/j.numecd.2021.03.008. | Intervention/Exposure; Duration
364 | Levitsky, DA, Halbmaier, CA, Mrdjenovic, et al. The freshman weight gain: a model for the study of the epidemic of obesity. Int J Obes Relat Metab Disord. 2004. 28:1435-42. doi:10.1038/sj.ijo.0802776. | Study design
365 | Levy, Julia. THE BREAKFAST RUSH. Health. 2019. 33:53-56. | Study design
366 | Li, C, Xing, C, Zhang, et al. Eight-hour time-restricted feeding improves endocrine and metabolic profiles in women withÂ anovulatory polycystic ovary syndrome. J Transl Med. 2021. 19:148. doi:10.1186/s12967-021-02817-2. | Intervention/Exposure
367 | Li, F, Harmer, P, Cardinal, et al. Built environment and 1-year change in weight and waist circumference in middle-aged and older adults: Portland Neighborhood Environment and Health Study. Am J Epidemiol. 2009. 169:401-8. doi:10.1093/aje/kwn398. | Intervention/Exposure
368 | Li, LB, Wang, N, Wu, et al. Energy Balance-related Behaviors Are Related to Cardiometabolic Parameters and Predict Adiposity in 8-14-year-old Overweight Chinese Children One Year Later. Biomed Environ Sci. 2016. 29:754-757. doi:10.3967/bes2016.100. | Intervention/Exposure
369 | Likhitweerawong, N, Boonchooduang, N, Kittisakmontri, et al. Effectiveness of mobile application on changing weight, healthy eating habits, and quality of life in children and adolescents with obesity: a randomized controlled trial. BMC Pediatr. 2021. 21:499. doi:10.1186/s12887-021-02980-x. | Intervention/Exposure
370 | Lin, Dan, Chen, Di-di, Huang, et al. Longitudinal association between the timing of adiposity peak and rebound and overweight at seven years of age. BMC Pediatr. 2022. 22:1-13. doi:10.1186/s12887-022-03190-9. | Study design
371 | Lin, TT, Guo, YL, Gordon, et al. Snacking among shiftwork nurses related to non-optimal dietary intake. J Adv Nurs. 2022. 78:3629-3640. doi:10.1111/jan.15253. | Study design; Outcome
372 | Lin, YJ, Wang, YT, Chan, et al. Effect of time-restricted feeding on body composition and cardio-metabolic risk in middle-aged women in Taiwan. Nutrition. 2022. 93:111504. doi:10.1016/j.nut.2021.111504. | Intervention/Exposure
373 | Linné, Y, Dye, L, Barkeling, et al. Weight development over time in parous women-the SPAWN study-15 years follow-up. Int J Obes Relat Metab Disord. 2003. 27:1516-22. doi:10.1038/sj.ijo.0802441. | Intervention/Exposure
374 | Liu, B, Hutchison, AT, Thompson, et al. Markers of adipose tissue inflammation are transiently elevated during intermittent fasting in women who are overweight or obese. Obes Res Clin Pract. 2019. 13:408-415. doi:10.1016/j.orcp.2019.07.001. | Intervention/Exposure
375 | Liu, Bo, Hutchison, AmyT, Thompson, et al. Weight loss and tissue remodelling following 8-week calorie restriction or intermittent fasting in females who are overweight and obese. Obes Res Clin Pract. 2019. 13:43-43. doi:10.1016/j.orcp.2016.10.058. | Intervention/Exposure; Publication status
376 | Lobene, AJ, Panda, S, Mashek, et al. Time-Restricted Eating for 12 Weeks Does Not Adversely Alter Bone Turnover in Overweight Adults. Nutrients. 2021. 13:. doi:10.3390/nu13041155. | Intervention/Exposure
377 | Lombardo, M, Bellia, A, Padua, et al. Morning meal more efficient for fat loss in a 3-month lifestyle intervention. J Am Coll Nutr. 2014. 33:198-205. doi:10.1080/07315724.2013.863169. | Intervention/Exposure; Comparator
378 | Loo, RSX, Yap, F, Ku, et al. Maternal meal irregularities during pregnancy and lifestyle correlates. Appetite. 2022. 168:105747. doi:10.1016/j.appet.2021.105747. | Study design; Intervention/Exposure; Outcome
379 | Lotti, S, Pagliai, G, Asensi, et al. Morning chronotype is associated with higher adherence to the Mediterranean diet in a sample of Italian adults. Nutr Metab Cardiovasc Dis. 2022. 32:2086-2092. doi:10.1016/j.numecd.2022.05.023. | Intervention/Exposure
380 | Lowe, DA, Wu, N, Rohdin-Bibby, et al. Effects of Time-Restricted Eating on Weight Loss and Other Metabolic Parameters in Women and Men With Overweight and Obesity: the TREAT Randomized Clinical Trial. JAMA Intern Med. 2020. 180:1491–1499. doi:10.1001/jamainternmed.2020.4153. | Intervention/Exposure
381 | Lowe, MR, Annunziato, RA, Markowitz, et al. Multiple types of dieting prospectively predict weight gain during the freshman year of college. Appetite. 2006. 47:83-90. doi:10.1016/j.appet.2006.03.160. | Intervention/Exposure
382 | Loy, SL, Cheng, TS, Colega, et al. Predominantly night-time feeding and maternal glycaemic levels during pregnancy. Br J Nutr. 2016. 115:1563-1570. doi:10.1017/s0007114516000441. | Intervention/Exposure; Comparator
383 | Lu, X, Fan, Z, Liu, et al. Extended Inter-Meal Interval Negatively Impacted the Glycemic and Insulinemic Responses after Both Lunch and Dinner in Healthy Subjects. Nutrients. 2022. 14:. doi:10.3390/nu14173617. | Intervention/Exposure; Comparator
384 | Lucassen, EA, Zhao, X, Rother, et al. Evening chronotype is associated with changes in eating behavior, more sleep apnea, and increased stress hormones in short sleeping obese individuals. PLoS One. 2013. 8:e56519. doi:10.1371/journal.pone.0056519. | Study design; Intervention/Exposure
385 | Lundgren, JD, Smith, BM, Spresser, et al. The relationship of night eating to oral health and obesity in community dental clinic patients. Gen Dent. 2010. 58:e134-9. | Study design; Outcome
386 | Lynch, S, Johnston, JD, Robertson, et al. Early versus late time-restricted feeding in adults at increased risk of developing type 2 diabetes: Is there an optimal time to eat for metabolic health?. Nutrition Bulletin. 2021. 46:69-76. doi:10.1111/nbu.12479. | Intervention/Exposure
387 | Lyzwinski, LN, Caffery, L, Bambling, et al. The Mindfulness App Trial for Weight, Weight-Related Behaviors, and Stress in University Students: Randomized Controlled Trial. JMIR Mhealth Uhealth. 2019. 7:e12210. doi:10.2196/12210. | Intervention/Exposure
388 | Ma, Y, Bertone, ER, Stanek, et al. Association between eating patterns and obesity in a free-living US adult population. Am J Epidemiol. 2003. 158:85-92. doi:10.1093/aje/kwg117. | Study design
389 | Madjd, A, Taylor, MA, Delavari, et al. Beneficial effect of high energy intake at lunch rather than dinner on weight loss in healthy obese women in a weight-loss program: a randomized clinical trial. Am J Clin Nutr. 2016. 104:982-989. doi:10.3945/ajcn.116.134163. | Comparator
390 | Madjd, A, Taylor, MA, Delavari, et al. Effects of consuming later evening meal v. earlier evening meal on weight loss during a weight loss diet: a randomised clinical trial. Br J Nutr. 2021. 126:632-640. doi:10.1017/s0007114520004456. | Intervention/Exposure; Comparator
391 | Madkour, MI, Malhab, LJB, Abdel-Rahman, et al. Ramadan Diurnal Intermittent Fasting Is Associated With Attenuated FTO Gene Expression in Subjects With Overweight and Obesity: A Prospective Cohort Study. Front Nutr. 2021. 8:741811. doi:10.3389/fnut.2021.741811. | Intervention/Exposure
392 | Maffeis, C, Grezzani, A, Perrone, et al. Could the savory taste of snacks be a further risk factor for overweight in children?. J Pediatr Gastroenterol Nutr. 2008. 46:429-37. doi:10.1097/MPG.0b013e318163b850. | Study design
393 | Magee, CA, Caputi, P, Iverson, et al. Patterns of health behaviours predict obesity in Australian children. J Paediatr Child Health. 2013. 49:291-6. doi:10.1111/jpc.12163. | Intervention/Exposure
394 | Magnusson MB, Hulthén L, Kjellgren KI. Obesity, dietary pattern and physical activity among children in a suburb with a high proportion of immigrants. J Hum Nutr Diet. 2005;18(3):187-194. doi:10.1111/j.1365-277X.2005.00604.x | Study design
395 | Mahmood, L, Gonzalez-Gil, EM, Makrilakis, et al. Cross-sectional and longitudinal associations between family meals frequency and children’s overweight/obesity in families at high risk of type 2 diabetes: The Feel4Diabetes-study. Pediatr Obes. 2023. 18:e13000. doi:10.1111/ijpo.13000. | Intervention/Exposure
396 | Makarem, Nour, Sears, DorothyD, St-Onge, et al. Variability in Daily Eating Patterns and Eating Jetlag Are Associated With Worsened Cardiometabolic Risk Profiles in the American Heart Association Go Red for Women Strategically Focused Research Network. J Am Heart Assoc. 2021. 10:1-12. doi:10.1161/JAHA.121.022024. | Intervention/Exposure
397 | Mallan, KM, Nambiar, S, Magarey, et al. Satiety responsiveness in toddlerhood predicts energy intake and weight status at four years of age. Appetite. 2014. 74:79-85. doi:10.1016/j.appet.2013.12.001. | Intervention/Exposure
398 | Manoogian, ENC, Zadourian, A, Lo, et al. Feasibility of time-restricted eating and impacts on cardiometabolic health in 24-h shift workers: The Healthy Heroes randomized control trial. Cell Metab. 2022. 34:1442-1456.e7. doi:10.1016/j.cmet.2022.08.018. | Study design; Intervention/Exposure
399 | Mansoori, A, Khosravi, M, Asadi, et al. Effects of evening meal timing on weight loss: A pilot open-labelled randomized clinical trial. Journal of Advances in Medical and Biomedical Research. 2020. 28:41-46. doi:10.30699/jambs.28.126.41. | Intervention/Exposure; Comparator
400 | Marinac, CR, Quante, M, Mariani, et al. Associations Between Timing of Meals, Physical Activity, Light Exposure, and Sleep With Body Mass Index in Free-Living Adults. J Phys Act Health. 2019. 16:214-221. doi:10.1123/jpah.2017-0389. | Study design
401 | Martínez-Lozano N, Tvarijonaviciute A, Ríos R, Barón I, Scheer FAJL, Garaulet M. Late Eating Is Associated with Obesity, Inflammatory Markers and Circadian-Related Disturbances in School-Aged Children. Nutrients. 2020;12(9):2881. Published 2020 Sep 21. doi:10.3390/nu12092881 | Intervention/Exposure; Comparator
402 | Martens, CR, Rossman, MJ, Mazzo, et al. Short-term time-restricted feeding is safe and feasible in non-obese healthy midlife and older adults. GeroScience. 2020. 42:667–686. doi:10.1007/s11357-020-00156-6. | Intervention/Exposure
403 | Martin, Lorena. Is Breakfast Related To Total Daily Calorie Intake And BMI In Middle School Latino Adolescents?. Med Sci Sports Exerc. 2011. 43:507-507. doi:10.1249/01.MSS.0000401397.01546.a9. | Study design; Publication status
404 | Martyn-Nemeth, P, Hayman, LL. Dietary Patterns and Meal Timing to Achieve a Healthy Body Weight and Promote Cardiometabolic Health: What Is the Evidence?. J Cardiovasc Nurs. 2023. 38:3-5. doi:10.1097/jcn.0000000000000954. | Study design
405 | Maughan, RJ, Bartagi, Z, Dvorak, et al. Dietary intake and body composition of football players during the holy month of Ramadan. J Sports Sci. 2008. 26 Suppl 3:S29-38. doi:10.1080/02640410802409675. | Intervention/Exposure
406 | Maukonen, M, Kanerva, N, Partonen, et al. Chronotype and energy intake timing in relation to changes in anthropometrics: a 7-year follow-up study in adults. Chronobiol Int. 2019. 36:27-41. doi:10.1080/07420528.2018.1515772. | Intervention/Exposure
407 | Maukonen, M, Kanerva, N, Partonen, et al. Chronotype differences in timing of energy and macronutrient intakes: A population-based study in adults. Obesity (Silver Spring). 2017. 25:608-615. doi:10.1002/oby.21747. | Study design; Intervention/Exposure
408 | Maukonen, M, Kanerva, N, Partonen, et al. The associations between chronotype, a healthy diet and obesity. Chronobiol Int. 2016. 33:972-81. doi:10.1080/07420528.2016.1183022. | Study design; Intervention/Exposure
409 | Mayra, ST, Chondropoulos, K, De Leon, et al. The feasibility and preliminary efficacy of early time-restricted eating on diet quality in college students: A randomized study. Obes Res Clin Pract. 2022. 16:413-420. doi:10.1016/j.orcp.2022.08.009. | Intervention/Exposure
410 | Mayra, ST, Kravat, N, Chondropoulos, et al. Early time-restricted eating may favorably impact cognitive acuity in university students: a randomized pilot study. Nutr Res. 2022. 108:1-8. doi:10.1016/j.nutres.2022.10.002. | Intervention/Exposure
411 | Mazri, FH, Manaf, ZA, Shahar, et al. Development and Evaluation of Integrated Chrono-Nutrition Weight Reduction Program among Overweight/Obese with Morning and Evening Chronotypes. Int J Environ Res Public Health. 2022. 19:. doi:10.3390/ijerph19084469. | Intervention/Exposure
412 | Mazri, FH, Manaf, ZA, Shahar, et al. Do Temporal Eating Patterns Differ in Healthy versus Unhealthy Overweight/Obese Individuals?. Nutrients. 2021. 13:. doi:10.3390/nu13114121. | Study design; Intervention/Exposure
413 | Mazri FH, Manaf ZA, Shahar S, Mat Ludin AF, Karim NA. Improvement in chrono-nutrition is associated with robust weight loss outcomes: An extension of the feasibility study. Chronobiol Int. 2023;40(3):272-283. doi:10.1080/07420528.2023.2165092 | Intervention/Exposure; Comparator
414 | McConahy, KL, Smiciklas-Wright, H, Birch, et al. Food portions are positively related to energy intake and body weight in early childhood. J Pediatr. 2002. 140:340-7. doi:10.1067/mpd.2002.122467. | Study design; Intervention/Exposure
415 | McCrory, MA, Howarth, NC, Roberts, et al. Eating frequency and energy regulation in free-living adults consuming self-selected diets. J Nutr. 2011. 141:148-153. doi:10.3945/jn.109.114991. | Study design
416 | McKiernan, F, Hollis, JH, Mattes, et al. Short-term dietary compensation in free-living adults. Physiol Behav. 2008. 93:975-83. doi:10.1016/j.physbeh.2007.12.014. | Intervention/Exposure
417 | McNeil, J, Lamothe, G, Cameron, et al. Investigating predictors of eating: is resting metabolic rate really the strongest proxy of energy intake?. Am J Clin Nutr. 2017. 106:1206-1212. doi:10.3945/ajcn.117.153718. | Intervention/Exposure
418 | Mekary, RA, Giovannucci, E, Cahill, et al. Eating patterns and type 2 diabetes risk in older women: breakfast consumption and eating frequency. Am J Clin Nutr. 2013. 98:436-43. doi:10.3945/ajcn.112.057521. | Outcome
419 | Mennella, JA, Smethers, AD, Decker, et al. Effects of Early Weight Gain Velocity, Diet Quality, and Snack Food Access on Toddler Weight Status at 1.5 Years: Follow-Up of a Randomized Controlled Infant Formula Trial. Nutrients. 2021. 13:. doi:10.3390/nu13113946. | Intervention/Exposure
420 | Meyer, AM, Evenson, KR, Couper, et al. Television, physical activity, diet, and body weight status: the ARIC cohort. Int J Behav Nutr Phys Act. 2008. 5:68. doi:10.1186/1479-5868-5-68. | Intervention/Exposure
421 | Meyer, U, Schindler, C, Bloesch, et al. Combined impact of negative lifestyle factors on cardiovascular risk in children: a randomized prospective study. J Adolesc Health. 2014. 55:790-5. doi:10.1016/j.jadohealth.2014.07.007. | Intervention/Exposure; Outcome
422 | Mielke, RuthT. Determinants of excessive gestational weight gain in Mexican American women in Los Angeles. . 2010:174 p-174 p. | Study design
423 | Miller, DP. Associations between the home and school environments and child body mass index. Soc Sci Med. 2011. 72:677-684. doi:10.1016/j.socscimed.2010.12.003. | Intervention/Exposure
424 | Milsom, VA, Middleton, KM, Perri, et al. Successful long-term weight loss maintenance in a rural population. Clin Interv Aging. 2011. 6:303-9. doi:10.2147/cia.S25389. | Study design
425 | Min, C, Noh, H, Kang, et al. Skipping breakfast is associated with diet quality and metabolic syndrome risk factors of adults. Nutr Res Pract. 2011. 5:455-63. doi:10.4162/nrp.2011.5.5.455. | Study design
426 | Mindru, DE, Moraru, E. Risk factors and their implications in the epidemiology of pediatric obesity. Rev Med Chir Soc Med Nat Iasi. 2012. 116:739-45. | Intervention/Exposure
427 | Mirmiran, P, Aghayan, M, Bakhshi, et al. Socioeconomic status and lifestyle factors modifies the association between snack foods intake and incidence of metabolic syndrome. Nutr J. 2021. 20:70. doi:10.1186/s12937-021-00728-y. | Intervention/Exposure; Outcome
428 | Mirmiran, P, Bahadoran, Z, Delshad, et al. Effects of energy-dense nutrient-poor snacks on the incidence of metabolic syndrome: a prospective approach in Tehran Lipid and Glucose Study. Nutrition. 2014. 30:538-43. doi:10.1016/j.nut.2013.09.014. | Intervention/Exposure; Outcome
429 | Mirzaei, A, Ghofranipour, F, Ghazanfar, et al. School children’s breakfast consumption: An educational intervention based on social cognitive theory. Annals of Tropical Medicine and Public Health. 2018:SP36. | Intervention/Exposure; Outcome
430 | Mizutani, T, Suzuki, K, Kondo, et al. Association of maternal lifestyles including smoking during pregnancy with childhood obesity. Obesity (Silver Spring). 2007. 15:3133-9. doi:10.1038/oby.2007.373. | Intervention/Exposure; Outcome
431 | Mogensen CS, Færch K, Bruhn L, et al. Timing and Frequency of Daily Energy Intake in Adults with Prediabetes and Overweight or Obesity and Their Associations with Body Fat. Nutrients. 2020;12(11):3484. Published 2020 Nov 13. doi:10.3390/nu12113484 | Study design
432 | Mok A, Haldar S, Lee JC, Leow MK, Henry CJ. Postprandial changes in cardiometabolic disease risk in young Chinese men following isocaloric high or low protein diets, stratified by either high or low meal frequency - a randomized controlled crossover trial. Nutr J. 2016;15:27. Published 2016 Mar 15. doi:10.1186/s12937-016-0141-5 | Outcome
433 | Molina-Montes E, Rodríguez-Barranco M, Ching-López A, et al. Circadian clock gene variants and their link with chronotype, chrononutrition, sleeping patterns and obesity in the European prospective investigation into cancer and nutrition (EPIC) study. Clin Nutr. 2022;41(9):1977-1990. doi:10.1016/j.clnu.2022.07.027 | Intervention/Exposure
434 | Montero, Manuel Dote, Sevilla-Lorente, Raquel, Merchan-Ramirez, et al. 35-LB: Effects of Three Different 8h Time-Restricted Eating Schedules over 4 Weeks on Body Weight and Waist/Hip Circumferences in Adults with Overweight/Obesity: A Pilot Randomized Trial. Diabetes. 2021. 70:N.PAG-N.PAG. doi:10.2337/db21-35-LB. | Intervention/Exposure; Publication status
435 | Moran, LisaJ, Brown, WendyJ, McNaughton, et al. Weight management practices associated with polycystic ovary syndrome and their relationships with diet and physical activity. Obes Res Clin Pract. 2019. 13:49-50. doi:10.1016/j.orcp.2016.10.067. | Study design; Publication status
436 | Moreno, LA, Kersting, M, de Henauw, et al. How to measure dietary intake and food habits in adolescence: the European perspective. Int J Obes (Lond). 2005. 29 Suppl 2:S66-77. doi:10.1038/sj.ijo.0803063. | Study design; Intervention/Exposure
437 | Morgan, LindaM, Jiang-Wen, Shi, Hampton, et al. Effect of meal timing and glycaemic index on glucose control and insulin secretion in healthy volunteers. Br J Nutr. 2012. 108:1286-1291. doi:10.1017/S0007114511006507. | Intervention/Exposure; Comparator
438 | Moro, T, Tinsley, G, Longo, et al. Time-restricted eating effects on performance, immune function, and body composition in elite cyclists: a randomized controlled trial. J Int Soc Sports Nutr. 2020. 17:65. doi:10.1186/s12970-020-00396-z. | Intervention/Exposure
439 | Moro, T, Tinsley, G, Pacelli, et al. Twelve Months of Time-restricted Eating and Resistance Training Improves Inflammatory Markers and Cardiometabolic Risk Factors. Med Sci Sports Exerc. 2021. 53:2577-2585. doi:10.1249/mss.0000000000002738. | Intervention/Exposure
440 | Morris, Alan. Breakfast not beneficial for weight loss. Nature Reviews Endocrinology. 2019. 15:190-190. doi:10.1038/s41574-019-0182-x. | Study design
441 | Morris, MA, Hutchinson, J, Gianfrancesco, et al. Relationship of the Frequency, Distribution, and Content of Meals/Snacks to Glycaemic Control in Gestational Diabetes: The myfood24 GDM Pilot Study. Nutrients. 2019. 12:. doi:10.3390/nu12010003. | Outcome
442 | Mota, MC, Waterhouse, J, De-Souza, et al. Association between chronotype, food intake and physical activity in medical residents. Chronobiol Int. 2016. 33:730-9. doi:10.3109/07420528.2016.1167711. | Study design
443 | Mou, Y, Jansen, PW, Raat, et al. Associations of family feeding and mealtime practices with children’s overall diet quality: Results from a prospective population-based cohort. Appetite. 2021. 160:105083. doi:10.1016/j.appet.2020.105083. | Outcome
444 | Mouchacca, J, Abbott, GR, Ball, et al. Associations between psychological stress, eating, physical activity, sedentary behaviours and body weight among women: a longitudinal study. BMC Public Health. 2013. 13:828. doi:10.1186/1471-2458-13-828. | Intervention/Exposure
445 | Mrdjenovic, G, Levitsky, DA. Children eat what they are served: the imprecise regulation of energy intake. Appetite. 2005. 44:273-82. doi:10.1016/j.appet.2005.01.005. | Study design
446 | Muñoz JSG, Cañavate R, Hernández CM, Cara-Salmerón V, Morante JJH. The association among chronotype, timing of food intake and food preferences depends on body mass status. Eur J Clin Nutr. 2017;71(6):736-742. doi:10.1038/ejcn.2016.182 | Intervention/Exposure
447 | Munsters, MJ, Saris, WH. Effects of meal frequency on metabolic profiles and substrate partitioning in lean healthy males. PLoS One. 2012. 7:e38632. doi:10.1371/journal.pone.0038632. | Outcome; Duration
448 | Muthayya, S, Thomas, T, Srinivasan, et al. Consumption of a mid-morning snack improves memory but not attention in school children. Physiol Behav. 2007. 90:142-50. doi:10.1016/j.physbeh.2006.09.025. | Comparator; Outcome
449 | Nagata, JM, Braudt, DB, Domingue, et al. Genetic risk, body mass index, and weight control behaviors: Unlocking the triad. Int J Eat Disord. 2019. 52:825-833. doi:10.1002/eat.23083. | Intervention/Exposure
450 | Nagata, JM, Garber, AK, Tabler, et al. Differential Risk Factors for Unhealthy Weight Control Behaviors by Sex and Weight Status Among U.S. Adolescents. J Adolesc Health. 2018. 63:335-341. doi:10.1016/j.jadohealth.2018.03.022. | Intervention/Exposure; Outcome
451 | Nagata, JM, Garber, AK, Tabler, et al. Disordered eating behaviors and cardiometabolic risk among young adults with overweight or obesity. Int J Eat Disord. 2018. 51:931-941. doi:10.1002/eat.22927. | Intervention/Exposure
452 | Nagata, K, Yoshida, M, Ishimoto, et al. Skipping breakfast and less exercise are risk factors for bone loss in young Japanese adults: a 3-year follow-up study. J Bone Miner Metab. 2014. 32:420-7. doi:10.1007/s00774-013-0510-5. | Outcome
453 | Nakajima, K, Higuchi, R, Mizusawa, et al. Unexpectedly High Prevalence of Breakfast Skipping in Low Body-Weight Middle-Aged Men: Results of the Kanagawa Investigation of Total Checkup Data from the National Data Base-7 (KITCHEN-7). Nutrients. 2020. 13:. doi:10.3390/nu13010102. | Study design
454 | Nas A, Mirza N, Hägele F, et al. Impact of breakfast skipping compared with dinner skipping on regulation of energy balance and metabolic risk. Am J Clin Nutr. 2017;105(6):1351-1361. doi:10.3945/ajcn.116.151332 | Comparator; Outcome
455 | Nascimento, M, Silva, D, Ribeiro, et al. Effect of a Nutritional Intervention in Athlete’s Body Composition, Eating Behaviour and Nutritional Knowledge: A Comparison between Adults and Adolescents. Nutrients. 2016. 8:. doi:10.3390/nu8090535. | Intervention/Exposure
456 | Naska, A, Orfanos, P, Trichopoulou, et al. Eating out, weight and weight gain. A cross-sectional and prospective analysis in the context of the EPIC-PANACEA study. Int J Obes (Lond). 2011. 35:416-26. doi:10.1038/ijo.2010.142. | Intervention/Exposure
457 | Nederkoorn, C, Houben, K, Hofmann, et al. Control yourself or just eat what you like? Weight gain over a year is predicted by an interactive effect of response inhibition and implicit preference for snack foods. Health Psychol. 2010. 29:389-93. doi:10.1037/a0019921. | Intervention/Exposure
458 | Nelson, MC, Gordon-Larsen, P, North, et al. Body mass index gain, fast food, and physical activity: effects of shared environments over time. Obesity (Silver Spring). 2006. 14:701-9. doi:10.1038/oby.2006.80. | Intervention/Exposure
459 | Neuhouser, ML, Patterson, RE, Kristal, et al. Do consumers of savory snacks have poor-quality diets?. J Am Diet Assoc. 2000. 100:576-9. doi:10.1016/s0002-8223(00)00176-0. | Study design; Intervention/Exposure
460 | Neumark-Sztainer, D, Eisenberg, ME, Fulkerson, et al. Family meals and disordered eating in adolescents: longitudinal findings from project EAT. Arch Pediatr Adolesc Med. 2008. 162:17-22. doi:10.1001/archpediatrics.2007.9. | Intervention/Exposure; Outcome
461 | Neumark-Sztainer, D, Wall, M, Guo, et al. Obesity, disordered eating, and eating disorders in a longitudinal study of adolescents: how do dieters fare 5 years later?. J Am Diet Assoc. 2006. 106:559-68. doi:10.1016/j.jada.2006.01.003. | Intervention/Exposure
462 | Neumark-Sztainer, D, Wall, M, Haines, et al. Why does dieting predict weight gain in adolescents? Findings from project EAT-II: a 5-year longitudinal study. J Am Diet Assoc. 2007. 107:448-55. doi:10.1016/j.jada.2006.12.013. | Intervention/Exposure; Outcome
463 | Neve, MJ, Morgan, PJ, Collins, et al. Behavioural factors related with successful weight loss 15 months post-enrolment in a commercial web-based weight-loss programme. Public Health Nutr. 2012. 15:1299-309. doi:10.1017/s1368980011003090. | Study design
464 | Newby, PK, Weismayer, C, Akesson, et al. Longitudinal changes in food patterns predict changes in weight and body mass index and the effects are greatest in obese women. J Nutr. 2006. 136:2580-7. doi:10.1093/jn/136.10.2580. | Intervention/Exposure
465 | Nisselson, HS. The Perils of Skipping Breakfast. J N J Dent Assoc. 2015. 86:4. | Study design
466 | Nonino-Borges, CB, Borges, RM, Bavaresco, et al. Influence of meal time on salivary circadian cortisol rhythms and weight loss in obese women. Nutrition. 2007. 23:385-391. doi:10.1016/j.nut.2007.02.007. | Intervention/Exposure; Comparator
467 | O’Brien, KM, Hutchesson, MJ, Jensen, et al. Participants in an online weight loss program can improve diet quality during weight loss: a randomized controlled trial. Nutr J. 2014. 13:82. doi:10.1186/1475-2891-13-82. | Intervention/Exposure
468 | Ochoa-Avilés A, Verstraeten R, Huybregts L, et al. A school-based intervention improved dietary intake outcomes and reduced waist circumference in adolescents: a cluster randomized controlled trial. Nutr J. 2017;16(1):79. Published 2017 Dec 11. doi:10.1186/s12937-017-0299-5 | Intervention/Exposure
469 | O’Connor, L, Brage, S, Griffin, et al. The cross-sectional association between snacking behaviour and measures of adiposity: the Fenland Study, UK. Br J Nutr. 2015. 114:1286-93. doi:10.1017/s000711451500269x. | Study design
470 | O’Dea, JA, Wagstaff, S. Increased breakfast frequency and nutritional quality among schoolchildren after a national breakfast promotion campaign in Australia between 2000 and 2006. Health Educ Res. 2011. 26:1086-96. doi:10.1093/her/cyr042. | Study design
471 | Oellingrath, IM, Svendsen, MV, Brantsaeter, et al. Tracking of eating patterns and overweight - a follow-up study of Norwegian schoolchildren from middle childhood to early adolescence. Nutr J. 2011. 10:106. doi:10.1186/1475-2891-10-106. | Intervention/Exposure
472 | Oellingrath, IM, Svendsen, MV. BMI-specific associations between health-related behaviours and overweight - a longitudinal study among Norwegian adolescents. Public Health Nutr. 2017. 20:481-491. doi:10.1017/s1368980016002536. | Intervention/Exposure
473 | Ogata, H, Hatamoto, Y, Goto, et al. Association between breakfast skipping and postprandial hyperglycaemia after lunch in healthy young individuals. Br J Nutr. 2019. 122:431-440. doi:10.1017/s0007114519001235. | Outcome
474 | Ogata, H, Kayaba, M, Tanaka, et al. Effect of skipping breakfast for 6 days on energy metabolism and diurnal rhythm of blood glucose in young healthy Japanese males. Am J Clin Nutr. 2019. 110:41-52. doi:10.1093/ajcn/nqy346. | Duration
475 | Oh, SY, Kim, BS, Choue, et al. Appetite sensations and eating behaviors to complete fasting in obese and non-obese individuals. Eur J Clin Nutr. 2002. 56:86-9. doi:10.1038/sj.ejcn.1601285. | Intervention/Exposure; Outcome
476 | Ohkawara, Kazunori, Cornier, Marc-Andre, Kohrt, et al. Effects of increased meal frequency on fat oxidation and perceived hunger. Obesity (19307381). 2013. 21:336-343. doi:10.1002/oby.20032. | Outcome; Duration
477 | Okubo, H, Crozier, SR, Harvey, et al. Diet quality across early childhood and adiposity at 6 years: the Southampton Women’s Survey. Int J Obes (Lond). 2015. 39:1456-62. doi:10.1038/ijo.2015.97. | Intervention/Exposure
478 | Olafsdottir, AS, Skuladottir, GV, Thorsdottir, et al. Maternal diet in early and late pregnancy in relation to weight gain. Int J Obes (Lond). 2006. 30:492-9. doi:10.1038/sj.ijo.0803184. | Intervention/Exposure
479 | Olson, CM, Strawderman, MS, Hinton, et al. Gestational weight gain and postpartum behaviors associated with weight change from early pregnancy to 1 y postpartum. Int J Obes. 2003. 27:117-127. doi:10.1038/sj.ijo.0802156. | Intervention/Exposure
480 | Olson, J, Aldrich, H, Callahan, et al. Characterization of Childhood Obesity andÂ Behavioral Factors. J Pediatr Health Care. 2016. 30:444-52. doi:10.1016/j.pedhc.2015.10.009. | Study design
481 | Orlet Fisher J, Rolls BJ, Birch LL. Children’s bite size and intake of an entrée are greater with large portions than with age-appropriate or self-selected portions. Am J Clin Nutr. 2003;77(5):1164-1170. doi:10.1093/ajcn/77.5.1164 | Intervention/Exposure
482 | Ovaskainen, ML, Tapanainen, H, Pakkala, et al. Changes in the contribution of snacks to the daily energy intake of Finnish adults. Appetite. 2010. 54:623-6. doi:10.1016/j.appet.2010.03.012. | Study design
483 | Péneau, S, Thibault, H, Meless, et al. Anthropometric and behavioral patterns associated with weight maintenance after an obesity treatment in adolescents. J Pediatr. 2008. 152:678-84. doi:10.1016/j.jpeds.2007.09.053. | Study design; Intervention/Exposure
484 | Pachucki, MA. Food pattern analysis over time: unhealthful eating trajectories predict obesity. Int J Obes (Lond). 2012. 36:686-94. doi:10.1038/ijo.2011.133. | Intervention/Exposure
485 | Palmer, MA, Capra, S, Baines, et al. Association between eating frequency, weight, and health. Nutr Rev. 2009. 67:379-390. doi:10.1111/j.1753-4887.2009.00204.x. | Study design
486 | Papageorgiou M, Biver E, Mareschal J, et al. The effects of time-restricted eating and weight loss on bone metabolism and health: a 6-month randomized controlled trial. Obesity (Silver Spring). 2023;31 Suppl 1(Suppl 1):85-95. doi:10.1002/oby.23577 | Intervention/Exposure
487 | Papakonstantinou, E, Kechribari, I, Mitrou, et al. Effect of meal frequency on glucose and insulin levels in women with polycystic ovary syndrome: a randomised trial. Eur J Clin Nutr. 2016. 70:588-94. doi:10.1038/ejcn.2015.225. | Health status
488 | Park, Song-Yi, Shvetsov, YuriiB, Kang, et al. Changes in Diet Quality over 10 Years Are Associated with Baseline Sociodemographic and Lifestyle Factors in the Multiethnic Cohort Study. J Nutr. 2020. 150:1880-1888. doi:10.1093/jn/nxaa102. | Intervention/Exposure
489 | Park, Su-Jeong, Yang, Jae-Won, Song, et al. The Effect of Four Weeks Dietary Intervention with 8-Hour Time-Restricted Eating on Body Composition and Cardiometabolic Risk Factors in Young Adults. Nutrients. 2021. 13:2164-2164. doi:10.3390/nu13072164. | Study design; Intervention/Exposure
490 | Parkes, KR. Demographic and lifestyle predictors of body mass index among offshore oil industry workers: cross-sectional and longitudinal findings. Occup Med (Lond). 2003. 53:213-21. doi:10.1093/occmed/kqg037. | Intervention/Exposure
491 | Parr, EB, Devlin, BL, Hawley, et al. Perspective: Time-Restricted Eating-Integrating the What with the When. Adv Nutr. 2022. 13:699-711. doi:10.1093/advances/nmac015. | Study design; Intervention/Exposure
492 | Parr, EB, Devlin, BL, Radford, et al. A Delayed Morning and Earlier Evening Time-Restricted Feeding Protocol for Improving Glycemic Control and Dietary Adherence in Men with Overweight/Obesity: a Randomized Controlled Trial. Nutrients. 2020. 12:. doi:10.3390/nu12020505. | Intervention/Exposure; Comparator
493 | Parr, EB, Kouw, IWK, Wheeler, et al. Eight-hour time-restricted eating does not lower daily myofibrillar protein synthesis rates: A randomized control trial. Obesity (Silver Spring). 2023. 31 Suppl 1:116-126. doi:10.1002/oby.23637. | Intervention/Exposure
494 | Parr, EvelynB, Dunstan, DavidW, Pinto, et al. Effects of a large breakfast versus large dinner on 24-h blood glucose profiles during a day of prolonged sedentary behaviour. Obes Res Clin Pract. 2019. 13:36-36. doi:10.1016/j.orcp.2016.10.043. | Intervention/Exposure; Publication status
495 | Patrick, K, Raab, F, Adams, et al. A text message-based intervention for weight loss: randomized controlled trial. J Med Internet Res. 2009. 11:e1. doi:10.2196/jmir.1100. | Intervention/Exposure
496 | Patterson, KAE, Ferrar, K, Gall, et al. Cluster patterns of behavioural risk factors among children: Longitudinal associations with adult cardio-metabolic risk factors. Prev Med. 2020. 130:105861. doi:10.1016/j.ypmed.2019.105861. | Intervention/Exposure
497 | Pearson, N, Griffiths, P, Biddle, et al. Individual, behavioural and home environmental factors associated with eating behaviours in young adolescents. Appetite. 2017. 112:35-43. doi:10.1016/j.appet.2017.01.001. | Study design
498 | Peeke, PM, Greenway, FL, Billes, et al. Effect of time restricted eating on body weight and fasting glucose in participants with obesity: results of a randomized, controlled, virtual clinical trial. Nutr Diabetes. 2021. 11:6. doi:10.1038/s41387-021-00149-0. | Intervention/Exposure; Comparator
499 | Peh, EWY, Koecher, K, Menon, et al. Breakfast consumption modulates postprandial glycaemic, insulinaemic and NEFA response in pre-diabetic Asian males. Br J Nutr. 2020. 123:664-672. doi:10.1017/s0007114519003180. | Outcome
500 | Peplonska, B, Kaluzny, P, Trafalska, et al. Rotating night shift work and nutrition of nurses and midwives. Chronobiol Int. 2019. 36:945-954. doi:10.1080/07420528.2019.1602051. | Study design
501 | Pereira, MA, Erickson, E, McKee, et al. Breakfast frequency and quality may affect glycemia and appetite in adults and children. J Nutr. 2011. 141:163-168. doi:10.3945/jn.109.114405. | Study design; Outcome
502 | Perrigue, MartineM, Drewnowski, Adam, Ching-Yun, et al. Higher Eating Frequency Does Not Decrease Appetite in Healthy Adults. J Nutr. 2016. 146:59-64. doi:10.3945/jn.115.216978. | Outcome
503 | Perrigue, MartineM, Drewnowski, Adam, Wang, et al. Randomized Trial Testing the Effects of Eating Frequency on Two Hormonal Biomarkers of Metabolism and Energy Balance. Nutr Cancer. 2017. 69:56-63. doi:10.1080/01635581.2017.1247888. | Duration
504 | Phelan, S, Wyatt, H, Nassery, et al. Three-year weight change in successful weight losers who lost weight on a low-carbohydrate diet. Obesity (Silver Spring). 2007. 15:2470-7. doi:10.1038/oby.2007.293. | Intervention/Exposure
505 | Pineda Vargas, SolangeS, O’Neil, CarolE, Keast, et al. Eating Ready-to-Eat Cereal for Breakfast is Positively Associated With Daily Nutrient Intake, but Not Weight, in Mexican-American Children and Adolescents. Nutr Today. 2016. 51:206-215. doi:10.1097/NT.0b013e3182993988. | Study design; Intervention/Exposure; Comparator
506 | Pinto, AM, Bordoli, C, Buckner, et al. Intermittent energy restriction is comparable to continuous energy restriction for cardiometabolic health in adults with central obesity: a randomized controlled trial; the Met-IER study. Clin Nutr. 2020. 39:1753–1763. doi:10.1016/j.clnu.2019.07.014. | Intervention/Exposure
507 | Pizinger, T, Kovtun, K, RoyChoudhury, et al. Pilot study of sleep and meal timing effects, independent of sleep duration and food intake, on insulin sensitivity in healthy individuals. Sleep Health. 2018. 4:33-39. doi:10.1016/j.sleh.2017.10.005. | Intervention/Exposure
508 | Polonsky, HM, Bauer, KW, Fisher, et al. Effect of a Breakfast in the Classroom Initiative on Obesity in Urban School-aged Children: A Cluster Randomized Clinical Trial. JAMA Pediatr. 2019. 173:326-333. doi:10.1001/jamapediatrics.2018.5531. | Intervention/Exposure
509 | Pot, GK, Hardy, R, Stephen, et al. Irregularity of energy intake at meals: prospective associations with the metabolic syndrome in adults of the 1946 British birth cohort. Br J Nutr. 2016. 115:315-23. doi:10.1017/s0007114515004407. | Intervention/Exposure
510 | Pouliot C, Biagé A, Prud’homme D, et al. Effect of weight status on dietary response to an 8-week aerobic exercise program in previously inactive adolescents. Obesity Medicine. 2021. 25:. doi:10.1016/j.obmed.2021.100363. | Intervention/Exposure
511 | Power, TG, Hidalgo-Mendez, J, Fisher, et al. Obesity risk in Hispanic children: Bidirectional associations between child eating behavior and child weight status over time. Eat Behav. 2020. 36:101366. doi:10.1016/j.eatbeh.2020.101366. | Intervention/Exposure
512 | Prasad, M, Fine, K, Gee, et al. A Smartphone Intervention to Promote Time Restricted Eating Reduces Body Weight and Blood Pressure in Adults with Overweight and Obesity: A Pilot Study. Nutrients. 2021. 13:. doi:10.3390/nu13072148. | Study design; Intervention/Exposure
513 | Purslow, LR, Sandhu, MS, Forouhi, et al. Energy intake at breakfast and weight change: prospective study of 6,764 middle-aged men and women. Am J Epidemiol. 2008. 167:188-92. doi:10.1093/aje/kwm309. | Study design; Intervention/Exposure; Other
514 | Queiroz JDN, Macedo RCO, Dos Santos GC, et al. Cardiometabolic effects of early v. delayed time-restricted eating plus energetic restriction in adults with overweight and obesity: an exploratory randomised clinical trial. Br J Nutr. Published online May 26, 2022. doi:10.1017/S0007114522001581 | Intervention/Exposure; Comparator
515 | Queiroz JDN, Macedo RCO, Dos Santos GC, et al. Cardiometabolic effects of early v. delayed time-restricted eating plus energetic restriction in adults with overweight and obesity: an exploratory randomised clinical trial. Br J Nutr. Published online May 26, 2022. doi:10.1017/S0007114522001581 | Intervention/Exposure; Comparator
516 | Rácz B, Dušková M, Stárka L, Hainer V, Kunešová M. Links between the circadian rhythm, obesity and the microbiome. Physiol Res. 2018;67(Suppl 3):S409-S420. doi:10.33549/physiolres.934020 | Study design
517 | Racette, SB, Deusinger, SS, Strube, et al. Weight changes, exercise, and dietary patterns during freshman and sophomore years of college. J Am Coll Health. 2005. 53:245-51. doi:10.3200/jach.53.6.245-251. | Intervention/Exposure
518 | Rafique, N. Body mass index, eating habits, and various lifestyle changes in young adults during the two years of the coronavirus disease 2019 (COVID-19) pandemic. J Family Community Med. 2022. 29:189-195. doi:10.4103/jfcm.jfcm_74_22. | Study design
519 | Rampersaud, GC, Pereira, MA, Girard, et al. Breakfast habits, nutritional status, body weight, and academic performance in children and adolescents. J Am Diet Assoc. 2005. 105:743-762. doi:10.1016/j.jada.2005.02.007. | Study design
520 | Rashidi, MR, Mahboob, S, Sattarivand, et al. Effects of nibbling and gorging on lipid profiles, blood glucose and insulin levels in healthy subjects. Saudi Med J. 2003. 24:945-8. | Intervention/Exposure; Outcome
521 | Rashidi, MR, Rahnama, B. Effect of meal frequency on human serum complements C3 and C4. Iran J Basic Med Sci. 2008. 11:49-54. doi:10.22038/IJBMS.2008.5196. | Outcome
522 | Ray, C, Roos, E. Family characteristics predicting favourable changes in 10 and 11-year-old children’s lifestyle-related health behaviours during an 18-month follow-up. Appetite. 2012. 58:326-32. doi:10.1016/j.appet.2011.10.009. | Intervention/Exposure; Outcome
523 | Raynor, HA, Li, F, Cardoso, et al. Daily pattern of energy distribution and weight loss. Physiol Behav. 2018. 192:167-172. doi:10.1016/j.physbeh.2018.02.036. | Comparator; Duration
524 | Raynor, HA, Niemeier, HM, Wing, et al. Effect of limiting snack food variety on long-term sensory-specific satiety and monotony during obesity treatment. Eat Behav. 2006. 7:1-14. doi:10.1016/j.eatbeh.2005.05.005. | Intervention/Exposure; Comparator
525 | Raynor, HA, Thomas, JG, Cardoso, et al. Examining the pattern of new foods and beverages consumed during obesity treatment to inform strategies for self-monitoring intake. Appetite. 2019. 132:147-153. doi:10.1016/j.appet.2018.10.018. | Intervention/Exposure
526 | Reeves, S, Huber, JW, Halsey, et al. A cross-over experiment to investigate possible mechanisms for lower BMIs in people who habitually eat breakfast. Eur J Clin Nutr. 2015. 69:632-7. doi:10.1038/ejcn.2014.269. | Outcome
527 | Reicks, Marla, Davey, Cynthia, Anderson, et al. P24 - Frequency of Eating Alone Among Adolescents was Associated with Parent Support, Dietary Intake and BMI: FLASHE Study Results. J Nutr Educ Behav. 2018. 50:S19-S19. doi:10.1016/j.jneb.2018.04.053. | Study design; Publication status
528 | Reid, KJ, Baron, KG, Zee, et al. Meal timing influences daily caloric intake in healthy adults. Nutr Res. 2014. 34:930-5. doi:10.1016/j.nutres.2014.09.010. | Study design
529 | Renault KM, Carlsen EM, Nørgaard K, et al. Intake of Sweets, Snacks and Soft Drinks Predicts Weight Gain in Obese Pregnant Women: Detailed Analysis of the Results of a Randomised Controlled Trial. PLoS One. 2015;10(7):e0133041. Published 2015 Jul 20. doi:10.1371/journal.pone.0133041 | Intervention/Exposure
530 | Richardson, CE, Tovar, AP, Davis, et al. An Intervention of Four Weeks of Time-Restricted Eating (16/8) in Male Long-Distance Runners Does Not Affect Cardiometabolic Risk Factors. Nutrients. 2023. 15:. doi:10.3390/nu15040985. | Intervention/Exposure
531 | Rito AI, Dinis A, Rascôa C, et al. Improving breakfast patterns of portuguese children-an evaluation of ready-to-eat cereals according to the European nutrient profile model. Eur J Clin Nutr. 2019;73(3):465-473. doi:10.1038/s41430-018-0235-6 | Outcome
532 | Roßbach S, Diederichs T, Bolzenius K, Herder C, Buyken AE, Alexy U. Age and time trends in eating frequency and duration of nightly fasting of German children and adolescents. Eur J Nutr. 2017;56(8):2507-2517. doi:10.1007/s00394-016-1286-x | Outcome
533 | Roberge, Jean-Baptiste, Van Hulst, Andraea, Barnett, et al. Lifestyle Habits, Dietary Factors, and the Metabolically Unhealthy Obese Phenotype in Youth. J Pediatr. 2019. 204:46-46. doi:10.1016/j.jpeds.2018.08.063. | Intervention/Exposure
534 | Robinson, WR, Stevens, J, Kaufman, et al. The role of adolescent behaviors in the female-male disparity in obesity incidence in US black and white young adults. Obesity (Silver Spring). 2010. 18:1429-36. doi:10.1038/oby.2009.362. | Intervention/Exposure
535 | Rollins, BY, Loken, E, Birch, et al. Preferences predict food intake from 5 to 11 years, but not in girls with higher weight concerns, dietary restraint, and %body fat. Obesity (Silver Spring). 2011. 19:2190-7. doi:10.1038/oby.2011.28. | Intervention/Exposure
536 | Rooney, Brenda, Mathiason, Michelle, Schauberger, et al. Predictors of Obesity in Childhood, Adolescence, and Adulthood in a Birth Cohort. Matern Child Health J. 2011. 15:1166-1175. doi:10.1007/s10995-010-0689-1. | Intervention/Exposure
537 | Rosenrauch, S, Ball, K, Lamb, et al. Associations between perceived friends’ support of healthy eating and meal skipping in adolescence. Public Health Nutr. 2017. 20:3266-3274. doi:10.1017/s136898001700235x. | Intervention/Exposure; Outcome
538 | Ross, KM, Qiu, P, You, et al. Week-to-week predictors of weight loss and regain. Health Psychol. 2019. 38:1150-1158. doi:10.1037/hea0000798. | Intervention/Exposure
539 | Ruddick-Collins, LC, Morgan, PJ, Fyfe, et al. Timing of daily calorie loading affects appetite and hunger responses without changes in energy metabolism in healthy subjects with obesity. Cell Metab. 2022. 34:1472-1485.e6. doi:10.1016/j.cmet.2022.08.001. | Intervention/Exposure; Comparator
540 | Sánchez-Villegas A, Martínez-González MA, Toledo E, de Irala-Estévez J, Martínez JA; Relative role of physical inactivity and snacking between meals in weight gain. Med Clin (Barc). 2002;119(2):46-52. doi:10.1016/s0025-7753(02)73311-3 | Study design; Language
541 | Saals, B, Boss, HM, Pot, et al. Young people and adolescents have more irregular meals during the COVID-19 pandemic: A nested case-control study on chrono-nutrition before and during the COVID-19 pandemic. Chronobiol Int. 2022. 39:991-1000. doi:10.1080/07420528.2022.2054347. | Intervention/Exposure; Outcome
542 | Saarilehto, S, Lapinleimu, H, Keskinen, et al. Growth, energy intake, and meal pattern in five-year-old children considered as poor eaters. J Pediatr. 2004. 144:363-7. doi:10.1016/j.jpeds.2003.12.028. | Study design; Intervention/Exposure
543 | Saini, SK, Singh, A, Saini, et al. Time-Restricted Eating Regimen Differentially Affects Circulatory miRNA Expression in Older Overweight Adults. Nutrients. 2022. 14:. doi:10.3390/nu14091843. | Intervention/Exposure
544 | Saldanha-Gomes C, Marbac M, Sedki M, et al. Clusters of diet, physical activity, television exposure and sleep habits and their association with adiposity in preschool children: the EDEN mother-child cohort. Int J Behav Nutr Phys Act. 2020;17(1):20. Published 2020 Feb 12. doi:10.1186/s12966-020-00927-6 | Intervention/Exposure
545 | Salunkhe, AH, Pratinidhi, A, Salunkhe, et al. Frequency and nutrient content of meals of the mothers and the birth weight and gestational age of the baby. Journal of Krishna Institute of Medical Sciences University. 2018. 7:33-41. | Outcome; Country
546 | Sandvik, P, Kuronen, S, Reijs Richards, et al. Associations of preschoolers’ dietary patterns with eating behaviors and parental feeding practices at a 12-month follow-up of obesity treatment. Appetite. 2022. 168:105724. doi:10.1016/j.appet.2021.105724. | Intervention/Exposure
547 | Santonja I, Bogl LH, Degenfellner J, et al. Meal-timing patterns and chronic disease prevalence in two representative Austrian studies. Eur J Nutr. 2023;62(4):1879-1890. doi:10.1007/s00394-023-03113-z | Study design
548 | Sari, DK, Marianne, . Impact of breakfast counselling and 6 days of breakfast on the nutritional status and knowledge of middle school students in berastagi, indonesia. Pakistan Journal of Nutrition. 2019. 19:12-18. doi:10.3923/pjn.2020.12.18. | Study design; Outcome
549 | Sartorelli, DS, Franco, LJ, Cardoso, et al. High intake of fruits and vegetables predicts weight loss in Brazilian overweight adults. Nutr Res. 2008. 28:233-8. doi:10.1016/j.nutres.2008.02.004 . | Intervention/Exposure
550 | Sata, M, Yamagishi, K, Sairenchi, et al. Impact of Caregiver Type for 3-Year-Old Children on Subsequent Between-Meal Eating Habits and Being Overweight From Childhood to Adulthood: A 20-Year Follow-up of the Ibaraki Children’s Cohort (IBACHIL) Study. J Epidemiol. 2015. 25:600-7. doi:10.2188/jea.JE20140078. | Intervention/Exposure
551 | Sata, M, Yamagishi, K, Sairenchi, et al. Long-term effect of feeding snacks at age 6 years on body mass index at ages 12 and 22 years. Sci Rep. 2019. 9:8627. doi:10.1038/s41598-019-40730-3. | Intervention/Exposure
552 | Savage, JS, Birch, LL. Patterns of weight control strategies predict differences in women’s 4-year weight gain. Obesity (Silver Spring). 2010. 18:513-20. doi:10.1038/oby.2009.265. | Intervention/Exposure; Outcome
553 | Savage, JS, Hoffman, L, Birch, et al. Dieting, restraint, and disinhibition predict women’s weight change over 6 y. Am J Clin Nutr. 2009. 90:33-40. doi:10.3945/ajcn.2008.26558. | Intervention/Exposure
554 | Scholtens, S, Brunekreef, B, Smit, et al. Do differences in childhood diet explain the reduced overweight risk in breastfed children?. Obesity (Silver Spring). 2008. 16:2498-503. doi:10.1038/oby.2008.403. | Intervention/Exposure
555 | Schusdziarra, V, Hausmann, M, Wiedemann, et al. Successful weight loss and maintenance in everyday clinical practice with an individually tailored change of eating habits on the basis of food energy density. Eur J Nutr. 2011. 50:351-61. doi:10.1007/s00394-010-0143-6. | Intervention/Exposure
556 | Schusdziarra, V, Hausmann, M, Wittke, et al. Contribution of energy density and food quantity to short-term fluctuations of energy intake in normal weight and obese subjects. Eur J Nutr. 2010. 49:37-43. doi:10.1007/s00394-009-0046-6. | Study design
557 | Schwedhelm, C, Lipsky, LM, Temmen, et al. Eating Patterns during Pregnancy and Postpartum and Their Association with Diet Quality and Energy Intake. Nutrients. 2022. 14:. doi:10.3390/nu14061167. | Study design
558 | Schwingel, A, Nakata, Y, Ito, et al. Central obesity and health-related factors among middle-aged men: a comparison among native Japanese and Japanese-Brazilians residing in Brazil and Japan. J Physiol Anthropol. 2007. 26:339-47. doi:10.2114/jpa2.26.339. | Intervention/Exposure
559 | Sedibe, MH, Pisa, PT, Feeley, et al. Dietary Habits and Eating Practices and Their Association with Overweight and Obesity in Rural and Urban Black South African Adolescents. Nutrients. 2018. 10:. doi:10.3390/nu10020145. | Study design; Country
560 | Sen, B. Frequency of family dinner and adolescent body weight status: evidence from the national longitudinal survey of youth, 1997. Obesity (Silver Spring). 2006. 14:2266-76. doi:10.1038/oby.2006.266. | Intervention/Exposure
561 | Shahar, DR, Schultz, R, Shahar, et al. The effect of widowhood on weight change, dietary intake, and eating behavior in the elderly population. J Aging Health. 2001. 13:189-99. doi:10.1177/089826430101300202. | Study design; Intervention/Exposure
562 | Shatenstein, B, Nadon, S, Ferland, et al. Determinants of diet quality among Quebecers aged 55-74. J Nutr Health Aging. 2004. 8:83-91. | Study design; Outcome
563 | Shaw, E, Dorrian, J, Coates, et al. Temporal pattern of eating in night shift workers. Chronobiol Int. 2019. 36:1613-1625. doi:10.1080/07420528.2019.1660358. | Study design; Intervention/Exposure
564 | Shriver, L, Marriage, B, Bloch, et al. Snacking Behaviors among Young Children: Examination of Snacking Across Racial/Ethnic Groups in the U.S. J Acad Nutr Diet. 2016. 116:A31-A31. doi:10.1016/j.jand.2016.06.105. | Publication status
565 | Siahpush, M, Tibbits, M, Shaikh, et al. Dieting Increases the Likelihood of Subsequent Obesity and BMI Gain: Results from a Prospective Study of an Australian National Sample. Int J Behav Med. 2015. 22:662-71. doi:10.1007/s12529-015-9463-5. | Intervention/Exposure
566 | Siedler, MR, Lewis, MH, Trexler, et al. The Effects of Intermittent Diet Breaks during 25% Energy Restriction on Body Composition and Resting Metabolic Rate in Resistance-Trained Females: A Randomized Controlled Trial. J Hum Kinet. 2023. 86:117-132. doi:10.5114/jhk/159960. | Intervention/Exposure
567 | Siega-Riz, AM, Herrmann, TS, Savitz, et al. Frequency of eating during pregnancy and its effect on preterm delivery. Am J Epidemiol. 2001. 153:647-52. doi:10.1093/aje/153.7.647. | Study design; Outcome
568 | Sila S, Ilić A, Mišigoj-Duraković M, Sorić M, Radman I, Šatalić Z. Obesity in Adolescents Who Skip Breakfast Is Not Associated with Physical Activity. Nutrients. 2019;11(10):2511. Published 2019 Oct 18. doi:10.3390/nu11102511 | Study design
569 | Simon, SL, Blankenship, J, Manoogian, et al. The impact of a self-selected time restricted eating intervention on eating patterns, sleep, and late-night eating in individuals with obesity. Front Nutr. 2022. 9:1007824. doi:10.3389/fnut.2022.1007824. | Intervention/Exposure
570 | Simon, SL, Pan, Z, Marden, et al. Body mass index and variability in meal duration and association with rate of eating. Front Nutr. 2022. 9:941001. doi:10.3389/fnut.2022.941001. | Study design; Intervention/Exposure
571 | Singh, RB, Cornelissen, G, Mojto, et al. Effects of circadian restricted feeding on parameters of metabolic syndrome among healthy subjects. Chronobiol Int. 2020. 37:395–402. doi:10.1080/07420528.2019.1701817. | Intervention/Exposure; Comparator
572 | Sitzman, K. Express speak. Eating breakfast helps sustain weight loss. AAOHN Journal. 2006. 54:136-136. doi:10.1177/216507990605400307. | Study design
573 | Skinner, JD, Ziegler, P, Pac, et al. Meal and snack patterns of infants and toddlers. J Am Diet Assoc. 2004. 104:s65-70. doi:10.1016/j.jada.2003.10.021. | Study design
574 | Skoczek-Rubińska A, Muzsik-Kazimierska A, Chmurzynska A, Walkowiak PJ, Bajerska J. Snacking may improve dietary fiber density and is associated with a lower body mass index in postmenopausal women. Nutrition. 2021;83:111063. doi:10.1016/j.nut.2020.111063 | Study design
575 | Slomski, A. Adding Time-Restricted Eating to Caloric Restriction for Weight Loss. Jama. 2022. 327:1950. doi:10.1001/jama.2022.8018. | Study design
576 | Smeets, AJ, Westerterp-Plantenga, MS. Acute effects on metabolism and appetite profile of one meal difference in the lower range of meal frequency. Br J Nutr. 2008. 99:1316-21. doi:10.1017/s0007114507877646. | Outcome
577 | Smith, KJ, McNaughton, SA, Gall, et al. Associations between Partnering and Parenting Transitions and Dietary Habits in Young Adults. J Acad Nutr Diet. 2017. 117:1210-1221. doi:10.1016/j.jand.2016.12.008. | Intervention/Exposure
578 | Soini, S, Mustajoki, P, Eriksson, et al. Weight loss methods and changes in eating habits among successful weight losers. Ann Med. 2016. 48:76-82. doi:10.3109/07853890.2015.1136428. | Study design; Outcome
579 | Solomon, TP, Chambers, ES, Jeukendrup, et al. The effect of feeding frequency on insulin and ghrelin responses in human subjects. Br J Nutr. 2008. 100:810-9. doi:10.1017/s000711450896757x. | Outcome
580 | Soreca, I, Wallace, ML, Hall, et al. The association between meal timing and frequency with cardiometabolic profile in patients with bipolar disorder. Acta Psychiatr Scand. 2016. 133:453-8. doi:10.1111/acps.12578. | Study design; Intervention/Exposure
581 | Steger, FL, Jamshed, H, Bryan, et al. Early time-restricted eating affects weight, metabolic health, mood, and sleep in adherent completers: A secondary analysis. Obesity (Silver Spring). 2023. 31 Suppl 1:96-107. doi:10.1002/oby.23614. | Intervention/Exposure
582 | Steger, FL, Jamshed, H, Martin, et al. Impact of early time-restricted eating on diet quality, meal frequency, appetite, and eating behaviors: A randomized trial. Obesity (Silver Spring). 2023. 31 Suppl 1:127-138. doi:10.1002/oby.23642. | Intervention/Exposure
583 | Stennett, M, Blokland, A, Watt, et al. Mid-adolescent ethnic variations in overweight prevalence in the UK Millennium Cohort Study. Eur J Public Health. 2021. 31:396-402. doi:10.1093/eurpub/ckab023. | Study design; Intervention/Exposure
584 | Stockman, NK, Schenkel, TC, Brown, et al. Comparison of energy and nutrient intakes among meals and snacks of adolescent males. Prev Med. 2005. 41:203-10. doi:10.1016/j.ypmed.2004.11.001. | Study design
585 | St-Onge, MP, Pizinger, T, Kovtun, et al. Sleep and meal timing influence food intake and its hormonal regulation in healthy adults with overweight/obesity. Eur J Clin Nutr. 2019. 72:76-82. doi:10.1038/s41430-018-0312-x. | Intervention/Exposure
586 | Stote, KS, Baer, DJ, Spears, et al. A controlled trial of reduced meal frequency without caloric restriction in healthy, normal-weight, middle-aged adults. Am J Clin Nutr. 2007. 85:981–988. doi:10.1093/ajcn/85.4.981. | Intervention/Exposure; Duration
587 | Stratton, MT, Tinsley, GM, Alesi, et al. Four weeks of time-restricted feeding combined with resistance training does not differentially influence measures of body composition, muscle performance, resting energy expenditure, and blood biomarkers. Nutrients. 2020. 12:. doi:10.3390/nu12041126. | Intervention/Exposure
588 | Strojny, Z, Rutkowski, R, Kanikowska, et al. No Significant Effect of the Individual Chronotype on the Result of Moderate Calorie Restriction for Obesity-A Pilot Study. Nutrients. 2021. 13:. doi:10.3390/nu13114089. | Intervention/Exposure; Comparator
589 | Stubbs, J, Brogelli, D, Pallister, et al. Behavioural and motivational factors associated with weight loss and maintenance in a commercial weight management programme. Open Obesity Journal. 2012. 4:35-43. doi:10.2174/1876823701204010035. | Study design
590 | Stunkard, AJ, Berkowitz, RI, Schoeller, et al. Predictors of body size in the first 2 y of life: a high-risk study of human obesity. Int J Obes Relat Metab Disord. 2004. 28:503-13. doi:10.1038/sj.ijo.0802517. | Population Life Stage; Intervention/Exposure
591 | Sudharsanan, N, Romano, S, Cunningham, et al. School Breakfast Receipt and Obesity among American Fifth- and Eighth-Graders. J Acad Nutr Diet. 2016. 116:599-607.e3. doi:10.1016/j.jand.2015.08.021. | Intervention/Exposure
592 | Sugimori, H, Yoshida, K, Izuno, et al. Analysis of factors that influence body mass index from ages 3 to 6 years: A study based on the Toyama cohort study. Pediatr Int. 2004. 46:302-10. doi:10.1111/j.1442-200x.2004.01895.x. | Study design
593 | Sugiura, T, Dohi, Y, Takagi, et al. Impacts of lifestyle behavior and shift work on visceral fat accumulation and the presence of atherosclerosis in middle-aged male workers. Hypertens Res. 2020. 43:235-245. doi:10.1038/s41440-019-0362-z. | Study design
594 | Sugiyama, S, Okuda, M, Sasaki, et al. Breakfast habits among adolescents and their association with daily energy and fish, vegetable, and fruit intake: a community-based cross-sectional study. Environ Health Prev Med. 2012. 17:408-14. doi:10.1007/s12199-012-0270-1. | Study design
595 | Sutton, EF, Beyl, R, Early, et al. Early Time-Restricted Feeding Improves Insulin Sensitivity, Blood Pressure, and Oxidative Stress Even without Weight Loss in Men with Prediabetes. Cell Metab. 2018. 27:1212-1221.e3. doi:10.1016/j.cmet.2018.04.010. | Intervention/Exposure; Comparator
596 | Svensson, M, Hult, M, van der Mark, et al. The change in eating behaviors in a Web-based weight loss program: a longitudinal analysis of study completers. J Med Internet Res. 2014. 16:e234. doi:10.2196/jmir.3131. | Intervention/Exposure
597 | Szpak A, Jamiołkowski J, Witana K. Overweight and obesity and their determinants among men from Podlasie region in the years 1987-1998. Rocz Akad Med Bialymst. 2005;50 Suppl 1:245-249. | Intervention/Exposure
598 | Taguchi, M, Hara, A, Murata, et al. Increasing Meal Frequency in Isoenergetic Conditions Does Not Affect Body Composition Change and Appetite During Weight Gain in Japanese Athletes. Int J Sport Nutr Exerc Metab. 2021. 31:109-114. doi:10.1123/ijsnem.2020-0139. | Outcome; Duration
599 | Taillie, Lindsey Smith, Dantong, Wang, Popkin, et al. Snacking Is Longitudinally Associated with Declines in Body Mass Index z Scores for Overweight Children, but Increases for Underweight Children. J Nutr. 2016. 146:1268-1275. doi:10.3945/jn.115.226803. | Country
600 | Taillie, LS, Afeiche, MC, Eldridge, et al. Increased Snacking and Eating Occasions Are Associated with Higher Energy Intake among Mexican Children Aged 2-13 Years. J Nutr. 2015. 145:2570-7. doi:10.3945/jn.115.213165. | Study design
601 | Tajima, M, Lee, JS, Watanabe, et al. Association between changes in 12 lifestyle behaviors and the development of metabolic syndrome during 1 year among workers in the Tokyo metropolitan area. Circ J. 2014. 78:1152-9. doi:10.1253/circj.cj-13-1082. | Outcome
602 | Tang, J, Dong, JY, Eshak, et al. Supper Timing and Cardiovascular Mortality: The Japan Collaborative Cohort Study. Nutrients. 2021. 13:. doi:10.3390/nu13103389. | Intervention/Exposure; Outcome
603 | Tang, X, Andres, A, West, et al. Eating behavior and weight gain during pregnancy. Eat Behav. 2020. 36:101364. doi:10.1016/j.eatbeh.2020.101364. | Intervention/Exposure
604 | Tani, Y, Asakura, K, Sasaki, et al. Higher proportion of total and fat energy intake during the morning may reduce absolute intake of energy within the day. An observational study in free-living Japanese adults. Appetite. 2015. 92:66-73. doi:10.1016/j.appet.2015.04.071. | Study design; Intervention/Exposure
605 | Tanofsky-Kraff, M, Cohen, ML, Yanovski, et al. A prospective study of psychological predictors of body fat gain among children at high risk for adult obesity. Pediatrics. 2006. 117:1203-9. doi:10.1542/peds.2005-1329. | Intervention/Exposure
606 | Tatone-Tokuda, F, Dubois, L, Ramsay, et al. Sex differences in the association between sleep duration, diet and body mass index: a birth cohort study. J Sleep Res. 2012. 21:448-60. doi:10.1111/j.1365-2869.2011.00989.x. | Intervention/Exposure; Outcome
607 | Taveras, EM, Rifas-Shiman, SL, Berkey, et al. Family dinner and adolescent overweight. Obes Res. 2005. 13:900-6. doi:10.1038/oby.2005.104. | Intervention/Exposure
608 | Teo, Reena, Pink, AimeeE, Cheon, et al. Snack intake mediates the relationship between social exclusion and body mass index. Appetite. 2022. 169:N.PAG-N.PAG. doi:10.1016/j.appet.2021.105565. | Publication status
609 | Teong, XT, Liu, K, Vincent, et al. Intermittent fasting plus early time-restricted eating versus calorie restriction and standard care in adults at risk of type 2 diabetes: a randomized controlled trial. Nat Med. 2023. 29:963–972. doi:10.1038/s41591-023-02287-7. | Intervention/Exposure
610 | Thomas, EA, Zaman, A, Cornier, et al. Later Meal and Sleep Timing Predicts Higher Percent Body Fat. Nutrients. 2020. 13:. doi:10.3390/nu13010073. | Intervention/Exposure
611 | Thomas, EA, Zaman, A, Sloggett, et al. Early time-restricted eating compared with daily caloric restriction: A randomized trial in adults with obesity. Obesity. 2022. 30:1027-1038. doi:10.1002/oby.23420. | Intervention/Exposure
612 | Thomas, JG, Bond, DS, Phelan, et al. Weight-loss maintenance for 10 years in the National Weight Control Registry. Am J Prev Med. 2014. 46:17-23. doi:10.1016/j.amepre.2013.08.019. | Intervention/Exposure
613 | Thompson, OM, Ballew, C, Resnicow, et al. Food purchased away from home as a predictor of change in BMI z-score among girls. Int J Obes Relat Metab Disord. 2004. 28:282-9. doi:10.1038/sj.ijo.0802538. | Intervention/Exposure
614 | Timko, CA, Mooney, K, Juarascio, et al. Change in eating and body related behaviors during the first year of university. Eat Weight Disord. 2010. 15:e93-7. doi:10.1007/bf03325286. | Intervention/Exposure
615 | Timlin MT, Pereira MA, Story M, Neumark-Sztainer D. Breakfast eating and weight change in a 5-year prospective analysis of adolescents: Project EAT (Eating Among Teens). Pediatrics. 2008;121(3):e638-e645. doi:10.1542/peds.2007-1035 | Duplicate
616 | Tin, SP, Ho, SY, Mak, et al. Location of breakfast consumption predicts body mass index change in young Hong Kong children. Int J Obes (Lond). 2012. 36:925-30. doi:10.1038/ijo.2011.262. | Comparator
617 | Tinsley, GM, Moore, ML, Graybeal, et al. Time-restricted feeding plus resistance training in active females: a randomized trial. Am J Clin Nutr. 2019. 110:628-640. doi:10.1093/ajcn/nqz126. | Intervention/Exposure
618 | Togo P, Osler M, Sørensen TI, Heitmann BL. A longitudinal study of food intake patterns and obesity in adult Danish men and women. Int J Obes Relat Metab Disord. 2004;28(4):583-593. doi:10.1038/sj.ijo.0802598 | Intervention/Exposure
619 | Torres, L, Lee, JL, Park, et al. Retention, Fasting Patterns, and Weight Loss With an Intermittent Fasting App: Large-Scale, 52-Week Observational Study. JMIR Mhealth Uhealth. 2022. 10:e35896. doi:10.2196/35896. | Intervention/Exposure
620 | Toyoshima, H, Masuoka, N, Hashimoto, et al. Effect of the interaction between mental stress and eating pattern on body mass index gain in healthy Japanese male workers. J Epidemiol. 2009. 19:88-93. doi:10.2188/jea.je20080066. | Study design; Intervention/Exposure
621 | Trier C, Fonvig CE, Bøjsøe C, et al. No influence of sugar, snacks and fast food intake on the degree of obesity or treatment effect in childhood obesity. Pediatr Obes. 2016;11(6):506-512. doi:10.1111/ijpo.12094 | Intervention/Exposure
622 | Tsuzaki J, Maskarinec G, Mapa V, et al. Diet Quality and Body Mass Index Over 20 Years in the Multiethnic Cohort. J Acad Nutr Diet. 2024;124(2):194-204. doi:10.1016/j.jand.2023.02.001 | Intervention/Exposure
623 | Tucker, LA, Bates, L. Restrained eating and risk of gaining weight and body fat in middle-aged women: a 3-year prospective study. Am J Health Promot. 2009. 23:187-94. doi:10.4278/ajhp.07061456. | Intervention/Exposure
624 | Turner-McGrievy, GM, Wirth, MD, Bernhart, et al. The Fasting and Shifted Timing (FAST) of Eating Study: A pilot feasibility randomized crossover intervention assessing the acceptability of three different fasting diet approaches. Appetite. 2022. 176:106135. doi:10.1016/j.appet.2022.106135. | Intervention/Exposure
625 | Unick, JL, Jakicic, JM, Marcus, et al. Contribution of behavior intervention components to 24-month weight loss. Med Sci Sports Exerc. 2010. 42:745-53. doi:10.1249/MSS.0b013e3181bd1a57. | Intervention/Exposure
626 | Van Elten TM, Van Poppel MNM, Gemke RJBJ, et al. Cardiometabolic Health in Relation to Lifestyle and Body Weight Changes 3⁻8 Years Earlier. Nutrients. 2018;10(12):1953. Published 2018 Dec 10. doi:10.3390/nu10121953 | Intervention/Exposure
627 | van Grieken, Amy, Vlasblom, Eline, Lu, et al. Personalized Web-Based Advice in Combination With Well-Child Visits to Prevent Overweight in Young Children: Cluster Randomized Controlled Trial. J Med Internet Res. 2017. 19:1-15. doi:10.2196/jmir.7115. | Intervention/Exposure
628 | van Rossum, CT, Hoebee, B, Seidell, et al. Genetic factors as predictors of weight gain in young adult Dutch men and women. Int J Obes Relat Metab Disord. 2002. 26:517-28. doi:10.1038/sj.ijo.0801964. | Intervention/Exposure
629 | Vanelli, M, Monti, G, Volta, et al. “GIOCAMPUS" - An effective school-based intervention for breakfast promotion and overweight risk reduction. Acta Biomed. 2014. 84:181-8. | Intervention/Exposure
630 | Veitsista, Alexandra, Laitinen, Jaana, Sovio, et al. Relationship between Eating Behavior, Breakfast Consumption, and Obesity Among Finnish and Greek Adolescents. J Nutr Educ Behav. 2010. 42:417-421. doi:10.1016/j.jneb.2009.12.004. | Study design
631 | Verbestel, V, De Coen, V, Van Winckel, et al. Prevention of overweight in children younger than 2 years old: a pilot cluster-randomized controlled trial. Public Health Nutr. 2014. 17:1384-92. doi:10.1017/s1368980013001353. | Intervention/Exposure
632 | Vergetaki, A, Linardakis, M, Papadaki, et al. Presence of metabolic syndrome and cardiovascular risk factors in adolescents and University students in Crete (Greece), according to different levels of snack consumption. Appetite. 2011. 57:278-85. doi:10.1016/j.appet.2011.05.309. | Study design
633 | Verma, N, Rastogi, S. Effects of time-restricted meals and risk of metabolic diseases. World Heart J. 2021. 13:59-60. | Study design; Intervention/Exposure
634 | Versteeg, RI, Ackermans, MT, Nederveen, et al. Meal timing effects on insulin sensitivity and intrahepatic triglycerides during weight loss. Int J Obes (Lond). 2018. 42:156-162. doi:10.1038/ijo.2017.199. | Comparator; Duration
635 | Versteeg, RI, Schrantee, A, Adriaanse, et al. Timing of caloric intake during weight loss differentially affects striatal dopamine transporter and thalamic serotonin transporter binding. Faseb j. 2017. 31:4545-4554. doi:10.1096/fj.201601234R. | Comparator; Duration
636 | Videon, TM, Manning, CK. Influences on adolescent eating patterns: the importance of family meals. J Adolesc Health. 2003. 32:365-73. doi:10.1016/s1054-139x(02)00711-5. | Study design; Intervention/Exposure
637 | Vidmar, AP, Jones, RB, Wee, et al. Timing of food consumption in Hispanic adolescents with obesity. Pediatr Obes. 2021. 16:e12764. doi:10.1111/ijpo.12764. | Study design
638 | Vidmar, AP, Naguib, M, Raymond, et al. Time-Limited Eating and Continuous Glucose Monitoring in Adolescents with Obesity: A Pilot Study. Nutrients. 2021. 13:. doi:10.3390/nu13113697. | Intervention/Exposure
639 | Vieira Musse, GN, Moreira, T, Ayumi Kimura, et al. Skipping breakfast concomitant with late-night dinner eating is associated with worse outcomes following ST-segment elevation myocardial infarction. Eur J Prev Cardiol. 2020. 27:2311-2313. doi:10.1177/2047487319839546. | Study design; Outcome; Health status
640 | Vilela, S, Oliveira, A, Ramos, et al. Association between energy-dense food consumption at 2 years of age and diet quality at 4 years of age. Br J Nutr. 2014. 111:1275-82. doi:10.1017/s0007114513003620. | Intervention/Exposure
641 | Vilela, S, Oliveira, A, Severo, et al. Chrono-Nutrition: The Relationship between Time-of-Day Energy and Macronutrient Intake and Children’s Body Weight Status. J Biol Rhythms. 2019. 34:332-342. doi:10.1177/0748730419838908. | Intervention/Exposure
642 | Vilela, S, Severo, M, Moreira, et al. Association between eating frequency and eating behaviours related to appetite from 4 to 7 years of age: Findings from the population-based birth cohort generation XXI. Appetite. 2019. 132:82-90. doi:10.1016/j.appet.2018.10.002. | Outcome
643 | Viskaal-van Dongen, M, Kok, FJ, de Graaf, et al. Effects of snack consumption for 8 weeks on energy intake and body weight. Int J Obes (Lond). 2010. 34:319-26. doi:10.1038/ijo.2009.243. | Intervention/Exposure; Comparator; Duration
644 | Vogels, N, Diepvens, K, Westerterp-Plantenga, et al. Predictors of long-term weight maintenance. Obes Res. 2005. 13:2162-8. doi:10.1038/oby.2005.268. | Intervention/Exposure
645 | Vujović N, Piron MJ, Qian J, et al. Late isocaloric eating increases hunger, decreases energy expenditure, and modifies metabolic pathways in adults with overweight and obesity. Cell Metab. 2022;34(10):1486-1498.e7. doi:10.1016/j.cmet.2022.09.007 | Intervention/Exposure; Comparator
646 | Wüenstel JW, Kowalkowska J, Wądołowska L, Słowińska MA, Niedźwiedzka E, Kurp L. Habitual eating of breakfast, consumption frequency of selected food and overweight prevalence in adolescents from various age groups. Dev Period Med. 2015;19(2):193-201. | Study design
647 | Waller, SM, Vander Wal, JS, Klurfeld, et al. Evening ready-to-eat cereal consumption contributes to weight management. J Am Coll Nutr. 2004. 23:316-21. doi:10.1080/07315724.2004.10719374. | Comparator
648 | Wang, Y, Ge, K, Popkin, et al. Why do some overweight children remain overweight, whereas others do not?. Public Health Nutr. 2003. 6:549-58. doi:10.1079/phn2003470. | Intervention/Exposure
649 | Webb, JB, Hardin, AS. A preliminary evaluation of BMI status in moderating changes in body composition and eating behavior in ethnically-diverse first-year college women. Eat Behav. 2012. 13:402-5. doi:10.1016/j.eatbeh.2012.06.004. | Intervention/Exposure
650 | Webber, KH, Lee, E. The diet quality of adult women participating in a behavioural weight-loss programme. J Hum Nutr Diet. 2011. 24:360-9. doi:10.1111/j.1365-277X.2011.01159.x. | Intervention/Exposure
651 | Wehrens, SMT, Christou, S, Isherwood, et al. Meal Timing Regulates the Human Circadian System. Curr Biol. 2017. 27:1768-1775.e3. doi:10.1016/j.cub.2017.04.059. | Comparator; Outcome
652 | Wei, X, Lin, B, Huang, et al. Effects of Time-Restricted Eating on Nonalcoholic Fatty Liver Disease: the TREATY-FLD Randomized Clinical Trial. JAMA network open. 2023. 6:e233513. doi:10.1001/jamanetworkopen.2023.3513. | Intervention/Exposure
653 | Wen, LM, Baur, LA, Rissel, et al. Correlates of body mass index and overweight and obesity of children aged 2 years: findings from the healthy beginnings trial. Obesity (Silver Spring). 2014. 22:1723-30. doi:10.1002/oby.20700. | Intervention/Exposure
654 | Wengreen, HJ, Moncur, C. Change in diet, physical activity, and body weight among young-adults during the transition from high school to college. Nutr J. 2009. 8:32. doi:10.1186/1475-2891-8-32. | Study design
655 | Wennberg, M, Gustafsson, PE, Wennberg, et al. Irregular eating of meals in adolescence and the metabolic syndrome in adulthood: results from a 27-year prospective cohort. Public Health Nutr. 2016. 19:667-73. doi:10.1017/s1368980015001445. | Intervention/Exposure
656 | Wennberg, M, Gustafsson, PE, Wennberg, et al. Poor breakfast habits in adolescence predict the metabolic syndrome in adulthood. Public Health Nutr. 2015. 18:122-9. doi:10.1017/s1368980013003509. | Intervention/Exposure
657 | Werneck, AO, Agostinete, RR, Cayres, et al. Association between Cluster of Lifestyle Behaviors and HOMA-IR among Adolescents: ABCD Growth Study. Medicina (Kaunas). 2018. 54:. doi:10.3390/medicina54060096. | Study design
658 | Westerberg, J, Edlund, B, Ghaderi, et al. A 2-year longitudinal study of eating attitudes, BMI, perfectionism, asceticism and family climate in adolescent girls and their parents. Eat Weight Disord. 2008. 13:64-72. doi:10.1007/bf03327605. | Intervention/Exposure
659 | Westerberg-Jacobson, J, Edlund, B, Ghaderi, et al. A 5-year longitudinal study of the relationship between the wish to be thinner, lifestyle behaviours and disturbed eating in 9-20year old girls. Eur Eat Disord Rev. 2010. 18:207-19. doi:10.1002/erv.983. | Intervention/Exposure
660 | Westerterp-Plantenga, MS, Kovacs, EM, Melanson, et al. Habitual meal frequency and energy intake regulation in partially temporally isolated men. Int J Obes Relat Metab Disord. 2002. 26:102-10. doi:10.1038/sj.ijo.0801855. | Study design; Intervention/Exposure
661 | Whetstone, LM, Kolasa, KM, Collier, et al. Participation in community-originated interventions is associated with positive changes in weight status and health behaviors in youth. Am J Health Promot. 2012. 27:10-6. doi:10.4278/ajhp.100415-QUAN-117. | Intervention/Exposure
662 | White, K, Wu, B, Pilla, et al. Design and Implementation of a Time-Restricted Eating Intervention in a Randomized, Controlled Eating Study. Nutrients. 2023. 15:. doi:10.3390/nu15081978. | Intervention/Exposure
663 | Wijga, AH, Scholtens, S, Bemelmans, et al. Diet, Screen Time, Physical Activity, and Childhood Overweight in the General Population and in High Risk Subgroups: Prospective Analyses in the PIAMA Birth Cohort. J Obes. 2010. 2010:. doi:10.1155/2010/423296. | Intervention/Exposure
664 | Wijtzes, AI, Jansen, W, Jaddoe, et al. Social Inequalities in Young Children’s Meal Skipping Behaviors: The Generation R Study. PLoS One. 2015. 10:e0134487. doi:10.1371/journal.pone.0134487. | Intervention/Exposure; Outcome
665 | Wilkinson, Michael, Manoogian, Emily, Zadourian, et al. TIME-RESTRICTED EATING PROMOTES WEIGHT LOSS AND LOWERS BLOOD PRESSURE IN PATIENTS WITH METABOLIC SYNDROME. Journal of the American College of Cardiology (JACC). 2019. 73:1843-1843. doi:10.1016/S0735-1097(19)32449-0. | Intervention/Exposure; Publication status
666 | Wilkinson, MJ, Manoogian, ENC, Zadourian, et al. Ten-Hour Time-Restricted Eating Reduces Weight, Blood Pressure, and Atherogenic Lipids in Patients with Metabolic Syndrome. Cell Metab. 2020. 31:92-104.e5. doi:10.1016/j.cmet.2019.11.004. | Intervention/Exposure
667 | Williams, SM, Taylor, RW, Taylor, et al. Secular changes in BMI and the associations between risk factors and BMI in children born 29 years apart. Pediatr Obes. 2013. 8:21-30. doi:10.1111/j.2047-6310.2012.00081.x. | Intervention/Exposure
668 | Wing, RR, Papandonatos, G, Fava, et al. Maintaining large weight losses: the role of behavioral and psychological factors. J Consult Clin Psychol. 2008. 76:1015-21. doi:10.1037/a0014159. | Intervention/Exposure
669 | Witbracht, M, Keim, NL, Forester, et al. Female breakfast skippers display a disrupted cortisol rhythm and elevated blood pressure. Physiol Behav. 2015. 140:215-21. doi:10.1016/j.physbeh.2014.12.044. | Outcome
670 | Wojcicki JM, Schwartz N, Jiménez-Cruz A, Bacardi-Gascon M, Heyman MB. Acculturation, dietary practices and risk for childhood obesity in an ethnically heterogeneous population of Latino school children in the San Francisco bay area. J Immigr Minor Health. 2012;14(4):533-539. doi:10.1007/s10903-011-9553-7 | Study design
671 | Woo, J, Cheung, B, Ho, et al. Influence of dietary pattern on the development of overweight in a Chinese population. Eur J Clin Nutr. 2008. 62:480-7. doi:10.1038/sj.ejcn.1602702. | Intervention/Exposure
672 | Woodruff, SJ, Hanning, RM, Lambraki, et al. Healthy Eating Index-C is compromised among adolescents with body weight concerns, weight loss dieting, and meal skipping. Body Image. 2008. 5:404-8. doi:10.1016/j.bodyim.2008.04.006. | Study design
673 | Woodruff, SJ, Hanning, RM. Effect of meal environment on diet quality rating. Can J Diet Pract Res. 2009. 70:118-24. doi:10.3148/70.3.2009.118. | Outcome
674 | Wright, CM, Cox, KM, Sherriff, et al. To what extent do weight gain and eating avidity during infancy predict later adiposity?. Public Health Nutr. 2012. 15:656-62. doi:10.1017/s1368980011002096. | Population Life Stage; Intervention/Exposure
675 | Wylie, J, Barr, S, Jeanes, et al. Eating frequency and snacking habits in women with polycystic ovary syndrome. J Hum Nutr Diet. 2009. 22:274-275. doi:10.1111/j.1365-277x.2009.00952_25.x. | Publication status
676 | Xiao, Q, Bauer, C, Layne, et al. The association between overnight fasting and body mass index in older adults: the interaction between duration and timing. Int J Obes (Lond). 2021. 45:555-564. doi:10.1038/s41366-020-00715-z. | Intervention/Exposure; Comparator
677 | Xiao, Q, Garaulet, M, Scheer, et al. Meal timing and obesity: interactions with macronutrient intake and chronotype. Int J Obes (Lond). 2019. 43:1701-1711. doi:10.1038/s41366-018-0284-x. | Intervention/Exposure
678 | Xie, Z, Sun, Y, Ye, et al. Randomized controlled trial for time-restricted eating in healthy volunteers without obesity. Nat Commun. 2022. 13:1003. doi:10.1038/s41467-022-28662-5. | Intervention/Exposure
679 | Xinyuan, Zhang, Yuntao, Wu, Muzi, et al. Habitual Night Eating Was Positively Associated With Progress of Arterial Stiffness in Chinese Adults. J Am Heart Assoc. 2020. 9:1-13. doi:10.1161/JAHA.120.016455. | Intervention/Exposure; Outcome
680 | Xu, S, Jiang, Y, Zhang, et al. Dietary recommendations for fasting days in an alternate-day intermittent fasting pattern: A randomized controlled trial. Nutrition. 2022. 102:111735. doi:10.1016/j.nut.2022.111735. | Intervention/Exposure
681 | Xue, H, Maguire, RL, Liu, et al. Snacking frequency and dietary intake in toddlers and preschool children. Appetite. 2019. 142:104369. doi:10.1016/j.appet.2019.104369. | Study design; Outcome
682 | Yan, Z, Harrington, A. Factors that predict weight gain among first-year college students. Health Educ J. 2020. 79:94-103. doi:10.1177/0017896919865758. | Study design
683 | Yasuda, J, Gomi, T, Kotemori, et al. Breakfast before resistance exercise lessens urinary markers of muscle protein breakdown in young men: A crossover trial. Nutrition. 2021. 83:. doi:10.1016/j.nut.2020.111088. | Intervention/Exposure; Outcome
684 | Yokoro, M, Wakimoto, K, Otaki, et al. Increased Prevalence of Breakfast Skipping in Female College Students in COVID-19. Asia Pac J Public Health. 2021. 33:438-440. doi:10.1177/1010539521998861. | Study design
685 | Yoon, C, Jacobs, DR, Jr, et al. Questionnaire-based problematic relationship to eating and food is associated with 25 year body mass index trajectories during midlife: The Coronary Artery Risk Development In Young Adults (CARDIA) Study. Int J Eat Disord. 2018. 51:10-17. doi:10.1002/eat.22813. | Intervention/Exposure
686 | Yoon, C, Mason, SM, Hooper, et al. Disordered Eating Behaviors and 15-year Trajectories in Body Mass Index: Findings From Project Eating and Activity in Teens and Young Adults (EAT). J Adolesc Health. 2020. 66:181-188. doi:10.1016/j.jadohealth.2019.08.012. | Intervention/Exposure
687 | Yoon, SR, Choi, M, Kim, et al. Effect of Breakfast Consumption and Meal Time Regularity on Nutrient Intake and Cardiometabolic Health in Korean Adults. J Lipid Atheroscler. 2021. 10:240-250. doi:10.12997/jla.2021.10.2.240. | Study design
688 | Yoshinaga, M, Hatake, S, Tachikawa, et al. Impact of lifestyles of adolescents and their parents on cardiovascular risk factors in adolescents. J Atheroscler Thromb. 2011. 18:981-90. doi:10.5551/jat.9514. | Study design
689 | Yoshizaki, T, Togo, F. Objectively measured chronotype and social jetlag are associated with habitual dietary intake in undergraduate students. Nutr Res. 2021. 90:36-45. doi:10.1016/j.nutres.2021.04.003. | Study design; Intervention/Exposure
690 | Yu, Hong-jie, Liu, Xiangxiang, Zheng, et al. Child neglect and eating habits in primary schoolchildren: A prospective study in Wuhan, China. Appetite. 2022. 168:N.PAG-N.PAG. doi:10.1016/j.appet.2021.105756. | Intervention/Exposure; Outcome
691 | Zakrzewski, JK, Gillison, FB, Cumming, et al. Associations between breakfast frequency and adiposity indicators in children from 12 countries. Int J Obes Suppl. 2015. 5:S80-8. doi:10.1038/ijosup.2015.24. | Study design
692 | Zakrzewski-Fruer, JK, Wells, EK, Crawford, et al. Physical activity duration but not energy expenditure differs between daily and intermittent breakfast consumption in adolescent girls: A randomized crossover trial. J Nutr. 2018. 148:236-244. doi:10.1093/JN/NXX055. | Outcome
693 | Zalewska, M, Maciorkowska, E. Dietary Habits and Physical Activity of 18-Year-Old Adolescents in Relation to Overweight and Obesity. Iran J Public Health. 2019. 48:864-872. | Study design
694 | Zappalá G, Platania, A, Bellia, et al. Eating habits and food intake in relation to adherence to the mediterranean diet, in adults living in the Island of Sicily. Med J Nutrition Metab. 2019. 12:271-281. doi:10.3233/MNM-190306. | Study design
695 | Zeb, Falak, Wu, Xiaoyue, Chen, et al. Effect of time-restricted feeding on metabolic risk and circadian rhythm associated with gut microbiome in healthy males. Br J Nutr. 2020. 123:1216-1226. doi:10.1017/S0007114519003428. | Intervention/Exposure
696 | Zerón-Rugerio MF, Longo-Silva G, Hernáez Á, Ortega-Regules AE, Cambras T, Izquierdo-Pulido M. The Elapsed Time between Dinner and the Midpoint of Sleep is Associated with Adiposity in Young Women. Nutrients. 2020;12(2):410. Published 2020 Feb 5. doi:10.3390/nu12020410 | Study design; Intervention/Exposure
697 | Zerva, A, Nassis, GP, Krekoukia, et al. Effect of eating frequency on body composition in 9-11-year-old children. Int J Sports Med. 2007. 28:265-70. doi:10.1055/s-2006-924349. | Study design
698 | Zha, Peijia, Mahat, Ganga, Chao, et al. Perceived Body Weight and Weight Management-Related Behaviors among Young Adults: Mediating Effects of Body Mass Index. American Journal of Health Education. 2022. 53:381-393. doi:10.1080/19325037.2022.2120120. | Study design; Intervention/Exposure; Outcome
699 | Zhang, LM, Liu, Z, Wang, et al. Randomized controlled trial for time-restricted eating in overweight and obese young adults. iScience. 2022. 25:104870. doi:10.1016/j.isci.2022.104870 . | Intervention/Exposure
700 | Zhao, L, Hutchison, AT, Liu, et al. Time-restricted eating alters the 24-hour profile of adipose tissue transcriptome in men with obesity. Obesity (Silver Spring). 2023. 31 Suppl 1:63-74. doi:10.1002/oby.23499. | Intervention/Exposure
701 | Zhao, L, Hutchison, AT, Liu, et al. Time-restricted eating improves glycemic control and dampens energy-consuming pathways in human adipose tissue. Nutrition. 2022. 96:111583. doi:10.1016/j.nut.2021.111583. | Intervention/Exposure
702 | Zhao, L, Hutchison, AT, Wittert, et al. Intermittent Fasting Does Not Uniformly Impact Genes Involved in Circadian Regulation in Women with Obesity. Obesity (Silver Spring). 2020. 28 Suppl 1:S63-s67. doi:10.1002/oby.22775. | Intervention/Exposure
703 | Zheng, J, Gao, L, Xue, et al. Eating-out behaviors, associated factors and associations with obesity in Chinese school children: findings from the childhood obesity study in China mega-cities. Eur J Nutr. 2021. 60:3003-3012. doi:10.1007/s00394-020-02475-y. | Intervention/Exposure
704 | Zilberter, T, Zilberter, EY. Breakfast: to skip or not to skip?. Front Public Health. 2014. 2:59. doi:10.3389/fpubh.2014.00059. | Study design