# Appendix 1 Abbreviations

Table A 1 List of abbreviations

Abbreviation | Full name
HHS | United States Department of Health and Human Services
HEI | Healthy Eating Index
NESR | Nutrition Evidence Systematic Review
USDA | United States Department of Agriculture