# References of the articles included in the systematic review

1 Arvizu M, Bjerregaard AA, Madsen MTB, Sodium Intake during Pregnancy, but Not Other Diet Recommendations Aimed at Preventing Cardiovascular Disease, Is Positively Related to Risk of Hypertensive Disorders of Pregnancy. J Nutr. 2020;150(1):159–166. doi:10.1093/jn/nxz197 31504673
2 Brantsaeter AL, Haugen MS, S.O., Torjusen H, A dietary pattern characterized by high intake of vegetables, fruits, and vegetable oils is associated with reduced risk of preeclampsia in nulliparous pregnant Norwegian women. J Nutr. 2009;139(6)doi:10.3945/jn.109.104968
3 Courtney AU, O’Brien EC, Crowley RK, DASH (Dietary Approaches to Stop Hypertension) dietary pattern and maternal blood pressure in pregnancy. J Hum Nutr Diet. 2020;33(5):686–697. doi:10.1111/jhn.12744 32196793
4 de Seymour JV, Beck KL, Conlon CA, An Investigation of the Relationship Between Dietary Patterns in Early Pregnancy and Maternal/Infant Health Outcomes in a Chinese Cohort. Front Nutr. 2022;9doi:10.3389/fnut.2022.775557
5 Ding Y, Xu F, Zhong C, Association between Chinese Dietary Guidelines Compliance Index for Pregnant Women and Risks of Pregnancy Complications in the Tongji Maternal and Child Health Cohort. Nutrients. 2021;13(3)doi:10.3390/nu13030829
6 Flor-Alemany M, Acosta P, Marín-Jiménez N, Baena-García L, Aranda P, Aparicio VA. Influence of the degree of adherence to the mediterranean diet and its components on cardiometabolic risk during pregnancy. The GESTAFIT project. Nutr Metab Cardiovasc Dis. 2021;31(8):2311–2318. doi:10.1016/j.numecd.2021.04.019 34112581
7 Fulay AP, Rifas-Shiman SL, Oken E, Perng W. Associations of the dietary approaches to stop hypertension (DASH) diet with pregnancy complications in Project Viva. Eur J Clin Nutr. 2018;72(10):1385–1395. doi:10.1038/s41430-017-0068-8 29339829
8 Flynn AC, Seed PT, Patel N, Dietary patterns in obese pregnant women; influence of a behavioral intervention of diet and physical activity in the UPBEAT randomized controlled trial. Int J Behav Nutr Phys Act. 2016;13. doi:10.1186/s12966-016-0450-2
9 Hajianfar H, Esmaillzadeh A, Feizi A, Shahshahan Z, Azadbakht L. The Association Between Major Dietary Patterns and Pregnancy-related Complications. Arch Iran Med. 2018;21(10):443–451.30415552
10 Hillesund ER, N.C. Ø, Engel SM, Associations of adherence to the New Nordic Diet with risk of preeclampsia and preterm delivery in the Norwegian Mother and Child Cohort Study (MoBa). Eur J Epidemiol. 2014;29(10):753–65. doi:10.1007/s10654-014-9948-6 25193741
11 Hillesund ER, Bere E, Sagedal LR, Pre-pregnancy and early pregnancy dietary behavior in relation to maternal and newborn health in the Norwegian Fit for Delivery study - a post hoc observational analysis. Food Nutr Res. 2018;62doi:10.29219/fnr.v62.1273
12 Hu J, Li L, Wan N, Associations of Dietary Patterns during Pregnancy with Gestational Hypertension: The “Born in Shenyang” Cohort Study. Nutrients. 2022;14(20)doi:10.3390/nu14204342
13 Ikem E, Halldorsson TI, Birgisdóttir BE, Rasmussen MA, Olsen SF, Maslova E. Dietary patterns and the risk of pregnancy-associated hypertension in the Danish National Birth Cohort: a prospective longitudinal study. BJOG. 2019;126(5):663–673. doi:10.1111/1471-0528.15593 30675768
14 Li M, Grewal J, Hinkle SN, Healthy dietary patterns and common pregnancy complications: a prospective and longitudinal study. Am J Clin Nutr. 2021;114(3):1229–1237. doi:10.1093/ajcn/nqab145 34075392
15 Jarman M, Mathe N, Ramazani F, Dietary Patterns Prior to Pregnancy and Associations with Pregnancy Complications. Nutrients. 2018;10(7)doi:10.3390/nu10070914
16 Makarem N, Chau K, Miller EC, Association of a Mediterranean Diet Pattern With Adverse Pregnancy Outcomes Among US Women. JAMA Netw Open. 2022;5(12):e2248165. doi:10.1001/jamanetworkopen.2022.48165 36547978
17 Miele M, Souza R, Calderon IM, Maternal Nutrition Status Associated with Pregnancy-Related Adverse Outcomes. Nutrients. 2021;13(7)doi:10.3390/nu13072398
18 Miller CA-O, Boushey C, Benny P, Diet quality predicts hypertensive disorders of pregnancy in Asian and Pacific Islander Cohort. Nutr Health. 2022:1–10. doi:10.1177/02601060221109668
19 Rifas-Shiman SL, W. R-EJ, Kleinman KP, Oken E, Gillman MW. Dietary quality during pregnancy varies by maternal characteristics in Project Viva: a US cohort. J Am Diet Assoc. 2009;109(6):1004–11. doi:10.1016/j.jada.2009.03.001 19465182
20 Timmermans S, R.P. S-T, Vujkovic M, Major dietary patterns and blood pressure patterns during pregnancy: the Generation R Study. Am J Obstet Gynecol. 2011;205(4):e1–12. doi:10.1016/j.ajog.2011.05.013
21 Torjusen H, Brantsæter AL, Haugen M, Reduced risk of pre-eclampsia with organic vegetable consumption: results from the prospective Norwegian Mother and Child Cohort Study. BMJ Open. 2014;4(9) doi:10.1136/bmjopen-2014-006143
22 Wiertsema CJ, Mensink-Bout SM, Duijts L, Mulders A, Jaddoe VWV, Gaillard R. Associations of DASH Diet in Pregnancy With Blood Pressure Patterns, Placental Hemodynamics, and Gestational Hypertensive Disorders. J Am Heart Assoc. 2021;10(1)doi:10.1161/JAHA.120.017503
23 Yee LM, Silver RM, Haas DM, Quality of periconceptional dietary intake and maternal and neonatal outcomes. Am J Obstet Gynecol. 2020;223(1)doi:10.1016/j.ajog.2020.01.042
24 Al Wattar BH, Dodds J, Placzek A, Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PloS Med. 2019;16(7)doi:10.1371/journal.pmed.1002857
25 Assaf-Balut C, García de la Torre N, Durán A, A Mediterranean diet with additional extra virgin olive oil and pistachios reduces the incidence of gestational diabetes mellitus (GDM): A randomized controlled trial: The St. Carlos GDM prevention study. PloS One. 2017;12(10)doi:10.1371/journal.pone.0185873
26 Assaf-Balut C, García de la Torre N, Duran A, A Mediterranean Diet with an Enhanced Consumption of Extra Virgin Olive Oil and Pistachios Improves Pregnancy Outcomes in Women Without Gestational Diabetes Mellitus: A Sub-Analysis of the St. Carlos Gestational Diabetes Mellitus Prevention Study. Ann Nutr Metab. 2019;74(1):69–79. doi:10.1159/000495793 30554220
27 Crovetto F, Crispi F, Casas R, Effects of Mediterranean Diet or Mindfulness-Based Stress Reduction on Prevention of Small-for-Gestational Age Birth Weights in Newborns Born to At-Risk Pregnant Individuals: The IMPACT BCN Randomized Clinical Trial. JAMA. 2021;326(21)doi:10.1001/jama.2021.20178
28 Dodd JM, Deussen AR, Louise J. A Randomised Trial to Optimise Gestational Weight Gain and Improve Maternal and Infant Health Outcomes through Antenatal Dietary, Lifestyle and Exercise Advice: The OPTIMISE Randomised Trial. Nutrients. 2019;11(12)doi:10.3390/nu11122911
29 Khoury J, T. H, Christophersen B, Tonstad S. Effect of a cholesterol-lowering diet on maternal, cord, and neonatal lipids, and pregnancy outcome: a randomized clinical trial. Am J Obstet Gynecol. 2005;193(4):1292–301. doi:10.1016/j.ajog.2005.05.016 16202717
30 Melero V, García de la Torre N, Assaf-Balut C, Effect of a Mediterranean Diet-Based Nutritional Intervention on the Risk of Developing Gestational Diabetes Mellitus and Other Maternal-Fetal Adverse Events in Hispanic Women Residents in Spain. Nutrients. 2020;12(11):3505. doi:10.3390/nu12113505 33202607
31 Zhao L, Zhang P, Zheng Q, Deka A, Choudhury R, Rastogi S. Does a MediDiet With Additional Extra Virgin Olive Oil and Pistachios Reduce the Incidence of Gestational Diabetes? Endocr Pract. 2022;28(2):135–141. doi:10.1016/j.eprac.2021.08.010 34481972