# Summary of conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee did not draw a conclusion statement^*^ for the systematic review question: “What is the relationship between dietary patterns consumed during pregnancy and risk of hypertensive disorders of pregnancy?”.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of hypertensive disorders of pregnancy because of substantial concerns with consistency, directness, and precision in the body of evidence. (Grade: Grade Not Assignable)

## Research recommendations

To more adequately assess the relationship between dietary patterns during pregnancy and risk of hypertensive disorders of pregnancy, additional research is needed that should:

1. Include populations representative of all Americans, such as diversity in race and/or ethnicity, SEP, disability status, and gender identity. Of note, no included studies reported including American Indian or Alaska Native participants and a single study included Native Hawaiians.
2. Clearly describe characteristics related to health disparities (e.g., racial or ethnic group, religion, socioeconomic status, gender, age, or mental health; cognitive, sensory, or physical disability; sexual orientation or gender identity; geographic location; substance use; or other characteristics historically linked to discrimination or exclusion).
3. Conduct well-designed and sufficiently powered trials where the isolated effect of the dietary pattern is on risk of hypertensive disorders of pregnancy and where the dietary patterns are described in sufficient detail.
4. Administer dietary assessments as early as possible in and multiple times throughout pregnancy, use validated and reliable assessment methods, such as multiple 24 hour recalls and food frequency questionnaires validated for the population, and provide clear information on the period of time captured by the assessments.
5. Consider stratifying analyses by race and/or ethnicity or SEP (or other social determinants of health) or account for these and other key confounders in methods and/or analyses.
  a. Consider treatment of GDM as a potential mediator in the relationship between dietary patterns consumed during pregnancy and HDP.
6. Include strong justification when controlling for variables that occur after the start of the exposure period (i.e., pregnancy) that could have been affected by the exposure, such as gestational weight gain.
7. In addition to other planned analyses, evaluate the dietary pattern against existing indices of dietary quality (e.g., Healthy Eating Index) to facilitate comparison across studies and carefully describe food groups in dietary patterns.
8. Collect information on prenatal supplementation, including nutrient types and amounts, and consider supplementation in study design and/or analytic plans.
9. Since practical considerations limit most studies on pregnancy to observational designs, detailed collection and reporting of characteristics, behaviors and their timing and accounting for these factors in the analysis is critical.

Table 7 Evidence examining the relationship between dietary patterns consumed during pregnancy and hypertensive disorders of pregnancy^a^

Study Characteristics | Intervention or Exposure and Outcome | Results | Confounders, Funding, and Summary
RCT
Al Wattar, 2019^24^; RCT, Parallel-arm, United; Kingdom, ESTEEM; Baseline N=1252; Analytic N= 1137 (Attrition: 9%); - Age (y): IG: 31.4±5.2; CG: 30.9±5.2; ○ >40 (%): IG: 3.9; CG: 3.1; - Race/Ethnicity (%): White: IG: 36.6; CG: 35.5; Asian: IG: 43.4; CG: 44.1; Black: IG: 16.4; CG: 17.2; Other: IG: 3.7; CG: 3.3; - Baseline BMI (%): 25-29.9: IG: 16.7; CG: 16.7; ≥30: IG: 69.1; CG: 69.6; - History of PE (%): IG: 3.7; CG: 4.8; - Current T1 or T2 DM (%): 0.0 | IG vs. CG; 24 h recall at baseline (~18 GW);; ESTEEM Q at 20, 24, 28, 32, and 36 GW; DP Description:; - Control (CG): Received usual care and antenatal dietary advice as per U.K. national recommendations; - Intervention (IG): High intake of nuts, EVOO, fruit, vegetables, non-refined grains, and legumes; moderate to high consumption of fish; low to moderate intake of poultry and dairy products; low consumption of red meat and processed meat; and avoidance of sugary drinks, fast food, and food rich in animal fat. Participants provided with 30 g/d of mixed nuts and 0.5 L/wk of EVOO.; Adherence: ESTEEM Q score did not differ between groups at baseline but was significantly higher in IG vs CG after the intervention.; - Positive components: Olive oil (as main fat and svg/d); Nuts (including peanuts) Vegetables; Fruit (including juice); Pulses; Fish or shellfish; White meat over red meat; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial sweets or pastries; Outcome and assessment methods: PE assessed at: >20 GW; [underlined: New onset PE:] Systolic BP ≥140 mm Hg or diastolic BP ≥90 mmHg (≥2 readings, 4–6 hr apart) and new onset proteinuria (spot urine PCR >30 mg/mmol, 24-hr urine protein >300 mg, or ≥2+ on urine dipstick); [underlined: Superimposed PE:] new onset proteinuria in participants w/ chronic HTN; Serum alanine aminotransferase concentration >70 U/L or worsening HTN in participants w/ chronic HTN AND proteinuria at baseline.; Eclamptic seizures w/ no HTN or proteinuria also considered PE. | Preeclampsia; Multivariable logistic regression aOR (95% CI); [underlined: All participants:] 1.43 (0.84, 2.43), p=0.19; [underlined: Baseline BMI ≥30:] 1.65 (0.88, 3.11), p≥0.05; [underlined: Baseline BMI ≥30:] 99 (0.37, 2.69), p.≥0.05; p for interaction=0.40; [underlined: Raised TG at baseline:] 1.13 (0.47, 2.71), p≥0.05; [underlined: Normal TG at baseline:] 1.21 (0.59, 2.46), p≥0.05; p for interaction=0.91; [underlined: Chronic HTN:] 3.62 (0.65, 20.01), p≥0.05; [underlined: No chronic HTN:] 1.26 (0.71, 2.24), p≥0.05 p for interaction=0.25 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP; Other covariates: Personal history of GDM, Family history of HDP, Family history of DM, History of stillbirth, Recruitment center; Funding: Barts Charity; California Walnut Commission and Blue Diamond Growers donated walnuts and almonds, respectively; Summary: In metabolically at risk participants, a simple, individualized, Mediterranean-style diet supplemented with mixed nuts and EVOO did not have a significant effect on risk of new onset or superimposed preeclampsia compared to usual care.
Assaf-Balut, 2017^25^ RCT, Parallel-arm, Spain, The St. Carlos GDM Prevention Study; Baseline N=1000; Analytic N= 874 (Attrition: 13%); - Age (y): CG: 32.7±5.3; IG: 33.2±5.0; - Race/Ethnicity (%): White: CG: 67.8; IG: 69.0; Hispanic: CG: 28.4; IG: 28.6; Other: CG: 3.8; IG: 2.4; - SEP:; ○ Education (%): Elementary: CG: 10.8; IG: 6.8; University: CG: 50.2; IG: 50.4; ○ Employment (%): CG: 75.2; IG: 78.0; - Pre-pregnancy BMI: CG: 23.3±4.0; IG: 22.9±3.6; - Current GDM (%): CG: 23.4; IG: 17.1, p=0.012; - Smoking (%): CG: 8.0; IG: 8.6 | IG vs. CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between groups at baseline. Scores significantly increased over time in both groups, but scores remaining significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcome and assessment methods:; BP assessed at: 24-28 GW and 36-38 GW;; Gestational HTN, PE, and Proteinuria assessed at: >20 GW; BP assessed while sitting after resting for 10 min.; [underlined: Gestational HTN:] ≥140 mmHg SBP/90 mmHg DBP; [underlined: PE:] ≥140 mmHg SBP/90 mmHg DBP w/ proteinuria ≥300 mg in 24h; [underlined: Proteinuria:] ≥300 mg in 24h w/ <140 mmHg SBP and <90 mm Hg DBP | Systolic BP; Student t test or Mann-Whitney U test Mean±SD, mmHg; [underlined: 24-28 GW:] CG: 105±11; IG: 105±11, p=0.189; [underlined: 36-38 GW:] CG: 112±13; IG: 112±11, p=0.193; Diastolic BP; Student t test or Mann-Whitney U test Mean±SD, mmHg; [underlined: 24-28 GW:] CG: 63±9; IG: 63±10, p=0.819; [underlined: 36-38 GW:] CG: 72±9; IG: 73±9, p=0.316; Gestational Hypertension; Chi-squared test, %; CG: 4.3; IG: 3.0, p=0.195; Preeclampsia; Chi-squared test, %; CG: 2.5; IG: 1.6, p=0.247; Proteinuria; Chi-squared test, %; CG: 1.4; IG: 0.5, p=0.298 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Fondo Europeo de Desarrollo Regiona; Summary: A MedDiet supplemented with EVOO and pistachios had no significant effect on systolic or diastolic blood pressure at either 24-28 or 36-38 GW, gestational hypertension, preeclampsia, or proteinuria.
Assaf-Balut, 2019^26^; RCT, Parallel-arm, Spain, St. Carlos GDM Prevention Study; Baseline N=823; Analytic N= 697 (Attrition: 15%); - Age (y): CG: 32.54±5.29; IG: 32.92±4.92; - Race/Ethnicity (%): White: CG: 67.1; IG: 67.8; Hispanic: CG: 29.1; IG: 30.3; Other: CG: 3.9; IG: 1.9; - SEP:; ○ Education (%): Elementary: CG: 7.6; IG: 6.1; University: CG: 50.1; IG: 51.4; ○ Employment (%): CG: 75.3; IG: 79.2; - Pre-pregnancy BMI: CG: 22.9±3.8; IG: 22.4±3.3; - Current GDM (%): 0.0; - Smoking (%): CG: 7.4; IG: 8.3 | IG vs. CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ at baseline. Scores significantly increased over time in both groups, but scores remained significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcome and assessment methods:; BP assessed at: 24-28 GW and 36-38 GW;; Gestational HTN, PE, and Proteinuria assessed at: >20 GW; BP assessed while sitting after resting for 10 min.; [underlined: Gestational HTN]: ≥140 mmHg SBP/90 mmHg DBP; [underlined: PE]: ≥140 mmHg SBP/90 mmHg DBP w/ proteinuria ≥300 mg in 24h; [underlined: Proteinuria:] ≥300 mg in 24h w/ <140 mmHg SBP and <90 mm Hg DBP | Systolic BP; Student t test or Mann-Whitney U test Mean diff (95% CI), mmHg; [underlined: 24-28 GW:] −1.5 (−3.2, 0.3), p=0.097; [underlined: 36-38 GW:] −0.9 (−3.5, 1.8), p=0.517; Diastolic BP; Student t test or Mann-Whitney U test Mean diff (95% CI), mmHg; [underlined: 24-28 GW]: −0.8 (−2.2, 0.6), p=0.279; [underlined: 36-38 GW:] −1.7 (−3.7, 0.1), p=0.068; Gestational Hypertension; Chi-squared test, %; CG: 3.3; IG: 3.6, p=0.484; Preeclampsia; Chi-squared test, %; CG: 1.2; IG: 1.9, p=0.311; Proteinuria; Chi-squared test, %; CG: 1.2; IG: 0.6, p=0.313 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Among normoglycemic participants, a MedDiet supplemented with EVOO and pistachios had no significant effect on systolic or diastolic BP at either 24-28 or 36-38 GW, gestational hypertension, preeclampsia, or proteinuria, although slightly higher diastolic blood pressure neared significance at 36-38 GW.
Crovetto, 2021^27^; RCT, Parallel-arm, Spain, IMPACT BCN; Baseline N=814; Analytic N= 793 (Attrition: 3%); - Age (y): Median (IQR): IG: 37.2 (34.5-40.4); CG: 37 (33.2-40.5); - Race/Ethnicity (%): White: IG: 80.1; CG: 78.8; Latin American: IG: 13.8; CG: 15.2; Maghreb: IG: 2.0; CG: 2.2; Asian: IG: 2.0; CG: 2.0; Black: IG: 2.0; CG: 1.7; - SEP:; ○ SES status (%): High: IG: 59.7; CG: 57.1; Low: IG: 5.1; CG: 7.2; - Pre-pregnancy BMI: IG: 24±4.8; CG: 23.9±4.8; - History of PE (%): IG: 6.6; CG: 5.2; - Current DM (%): IG: 5.4; CG: 4.0; - Smoking (%): IG: 6.9; CG: 9.5 | IG vs. CG; FFQ and 7d diet journal at: 19-23.6 GW and 34-36 GW; DP Description:; - Intervention group (IG): Participants received dietary training and personalized advice to increase adherence to the Mediterranean diet, including increasing intake of whole grain cereals (≥5 svg/d); vegetables and dairy products (≥3 svg/d); fresh fruit (≥2 svg/d) including natural fruit juices; and legumes, nuts, fish, and white meat (≥3 svg/wk), as well as olive oil use for cooking and dressings. They also received olive oil (2 L/mo) and walnuts (450 g/mo).; - Control group (CG): Participants received usual care per institutional protocols.; Adherence: Mediterranean diet scores were similar between groups at baseline, but significantly increased in the IG at follow-up compared to the CG.; - Positive components: EVOO; walnuts; vegetables; fresh fruit; dairy products; whole grains; sofrito; legumes; fish; fatty fish; white meat; - Negative components: Refined grains; red meat; processed meat; soda drinks; commercial bakery foods, sweets, and pastries; butter, margarine, or cream; Outcome and assessment methods:; BP assessed at: 19-23.6 GW and 34-36 GW; PE assessed at: ≥20 GW; Gestational HTN, Eclampsia, HELLP assessed at: NR; BP measured by dietitian.; [underlined: PE]: SBP ≥140mmHg or DBP ≥90mmHg ≥4h apart and proteinuria ≥300 mg/24 h; [underlined: Gestational HTN, Eclampsia, HELLP:] Recorded within 28d after delivery | Preeclampsiaaccording to ITT analysis; Logistic regression; Risk difference (95% CI); OR (95% CI); -3.6 (−7.3, 0.0); 0.58 (0.34, 1.01), p=0.05; Preeclampsiaaccording to PP analysis Logistic regression; OR (95% CI); IG: Participants with high dietary adherence (3pt increase in diet score); 0.55 (0.29, 1.07), p=0.08; Mean Blood Pressure; ANCOVA; Mean diff (95% CI); 1.3 (0.3, 2.4), p<0.05; Gestational HTN; Chi-squared, %; IG: 2.0; CG: 2.3, p=0.84; Eclampsia; Chi-squared, %; IG: 0.3; CG: 0.0, p=0.31; HELLP; Chi-squared, %; IG: 0.3; CG: 0.0, p=0.31 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP; Funding: “La Caixa” Foundation; Cerebra Foundation for the Brain Injured Child; The Agency for Management of University and Research Grants; Centro de Investigaciones Biomédicas en Red sobre Enfermedades Raras; Summary: A Mediterranean-style DP supplemented with walnuts and EVOO did not have a significant effect on risk of preeclampsia or incidence of gestational hypertension, eclampsia, or HELLP syndrome. The intervention increased mean blood pressure from baseline to follow-up in the IG compared to the CG.
Dodd, 2019^28^; RCT, Parallel-arm, Australia, OPTIMISE; Baseline N=641; Analytic N= 629 (Attrition: 1%); - Age (y): 31.53±4.76; - Race/Ethnicity (%): White: 67.46; Asian: 15.01; Indian, Pakistani, Sri Lankan: 8.06; Other: 9.47; - SEP:; ○ SEIFA IRSD (%): Quintile 1 (most disadvantaged): 16.75; Quintile 5: 17.85; - Baseline BMI: Median (IQR): 22.20 (20.87, 23.60); - Smoking (%): 4.42 | LI vs. SC; FFQ at: Trial entry (10-20 GW), 28 GW, and 36 GW; DP Description:; - Lifestyle Intervention (LI): Received 3 in-person visits and 3 phone calls with dietitian or research assistant at trial entry, and 20, 24, 28, 32, and 36 GW. Dietary advice was consistent with current Australian dietary standards, maintaining a balance of carbohydrates, fat, and protein, and encouraging reduced intake of energy dense and non-core foods high in refined carbohydrates and saturated fats. Participants were advised to increase their intake of fiber, and to consume 2 svg/d fruit, 5 svg/d vegetables and 3 svg/d dairy.; - Standard Care (SC): Received antenatal care according to hospital guidelines, which did not include information relating to dietary intake, physical activity or weight gain during pregnancy.; Adherence: HEI scores from FFQ did not differ at baseline but were higher in LI at 28 GW and 36 GW. Physical activity scores did not differ at either follow-up.; Outcome and assessment methods:; PE and Gestational HTN assessed at: >20 GW; [underlined: Gestational HTN]: Systolic BP ≥140 mmHg and/or diastolic BP ≥90 mmHg; PE: Gestational HTN and (≥1): proteinuria (300 mg/24h or spot urine protein/creatinine ratio ≥30 mg/mmol); renal insufficiency (serum/plasma creatinine ≥0.09 mmol/L or oliguria); liver disease; neurological problems; hematological disturbances; fetal growth restriction | Gestational Hypertension; Log Binomial Regression; OR (95% CI); 1.87 (0.52, 6.70), p=0.338; Preeclampsia; Log Binomial Regression; OR (95% CI); 0.70 (0.25, 1.96), p=0.502 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Funding: The University of Adelaide; Lloyd Cox Strategic Research Excellence Award; NHMRC Practitioner Fellowship; Summary: A lifestyle intervention with dietary advice consistent with Australian dietary standards had no significant on risk of gestational hypertension or preeclampsia compared to standard care.
Khoury, 2005^29^; RCT, Parallel-arm, Norway, CARRDIP; Baseline N=290; Analytic N=269 (Attrition: 7%); - Age (y): CG: 29.8±3.4; IG: 29.6±3.7; - SEP:; ○ Education >12y (%): CG: 84.6; IG: 79.4; - Baseline BMI: CG: 24.3±2.7; IG: 24.3±2.9; - High-risk pregnancies caused by DM (%): 0.0; - Smoking (%): 0.0 | IG vs. CG; Weighed food record at: 4d during 19-24 GW, 6d during 24-30 GW and 30-36 GW; - Intervention (IG): Diet aimed to aimed to limit dietary cholesterol to 150 mg/d and replace SFA by MUFA and PUFA. Participants encouraged to consume fatty fish, vegetable oils, especially olive oil and rapeseed oil, nuts, nut butters, margarine based on olive- or rapeseed oil, and avocado to replace meat, butter, cream, and fatty dairy products; fresh fruits and vegetables (≥6∕d); skimmed or low-fat dairy products in place of full fat products; meat for a main meal twice a week and use legumes, vegetable main dishes, fatty fish, or poultry with the fat trimmed off on the other days; coffee was limited to 2 cups of filtered coffee a day. Cooking lessons scheduled to implement special foods (e.g., legumes, olive oil).; - Control (CG): Usual diet based on Norwegian foodstuffs. Participants were asked to not to introduce more oils or low-fat meat and dairy products than usual.; Adherence: During the study period, the IG consumed significantly more fish and fish products, including fatty fish; rapeseed-based margarine; oils, including olive oil and rapeseed oil; nuts, olives, and seeds; vegetables; and fruits during the study period, as well as significantly less fatty milk; meat and meat products; fatty minced meat; butter; and hard margarines compared to the CG; Outcome and assessment methods:; HDP assessed at: >20 GW; Obtained from hospital records.; HDP: Gestational HTN (BP >140/90 mmHg at 2 occasions ≥6h apart) w/or w/o proteinuria (1+ on a dipstick assay) | HDP; Fisher exact test; OR (95% CI); 1.0 (0.5, 2.5), p=1.0 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP; Funding: The Norwegian Council on Cardiovascular Disease; Summary: A cholesterol-lowering diet did not have a significant effect on risk of hypertensive disorders of pregnancy.
Melero, 2020^30^; RCT, Parallel-arm, Spain, St. Carlos GDM prevention study; Baseline N=600; Analytic N= 260 (Attrition: 9%); - Age (y): CG: 31.3±5.6; IG: 31.7±5.4; - Race/Ethnicity (%): Hispanic: 100; - SEP:; ○ Education (%): Elementary: CG: 19.7; IG: 12.6; Secondary: CG: 47.2; IG: 46.2; University: CG: 31.7; IG: 40.6; Unknown: CG: 1.4; IG: 0.7; ○ Unemployed (%): CG: 69.0; IG: 67.8; - Pre-pregnancy BMI: CG: 24.4±4.0; IG: 24.1±3.4; - Current GDM (%): CG: 25.8; IG: 14.8, p=0.021 | IG vs. CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg legumes/wk, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts. | Systolic BP; Student t test or Mann-Whitney U test if normal distribution; Shapiro-Wilk test if not-normal distribution; Mean±SD, mmHg; [underlined: 24-28 GW:] CG: 104±11; IG: 106±11, p=0.131; [underlined: 36-38 GW:] CG: 115±16; IG: 113±13, p=0.631; Diastolic BP; Student t test or Mann-Whitney U test if normal distribution; Shapiro-Wilk test if not-normal distribution; Mean±SD, mmHg; [underlined: 24-28 GW:] CG: 63±9; IG: 63±9, p=0.864; [underlined: 36-38 GW:] CG: 72±9; IG: 72±9, p=0.192; Gestational Hypertension; Chi-squared test, % | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Among Hispanic participants, a MedDiet supplemented with EVOO and pistachios (IG) did not have an effect on systolic blood pressure or diastolic blood pressure at 24-28 GW or 36-38 GW, gestational hypertension, preeclampsia, or proteinuria compared to lower alignment with a MedDiet (CG).
- Smoking (%): CG: 0.7; IG: 0.7 | Adherence: MEDAS scores did not differ between the groups at baseline. Scores significantly increased over time in the IG, while no changes in the CG were observed. Scores remaining significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; - Negative components: commercial pastries; red meat or sausages; animal fat; sugar-sweetened beverages; - Alcohol and fruit (including juice) component excluded; Outcome and assessment methods:; BP assessed at: 24-28 GW and 36-38 GW;; Gestational HTN, PE, and Proteinuria assessed at: >20 GW; BP assessed while sitting after resting for 10 min.; [underlined: Gestational HTN:] >140 mmHg SBP or >90 mmHg DBP; [underlined: PE:] Gestational HTN w/ proteinuria (>300 mg in 24h); [underlined: Proteinuria:] >300 mg in 24h w/o gestational HTN | CG: 6.1; IG: 5.5, p=0.525; Preeclampsia; Chi-squared test, %; CG: 4.5; IG: 3.9, p=0.521; Proteinuria; Chi-squared test, %; CG: 2.3; IG: 0.0, p=0.129
Zhao, 2022^31^; RCT, Parallel-arm, China, People’s Hospital of Zhengzhou University; Baseline N=560; Analytic N= 500 (Attrition: 11%); - Age (y): CG: 28±5.2; IG: 29.4±5.6; - SEP:; ○ Employed (%): CG: 75.2; IG: 46.4; ○ Education (%) High school: CG: 0.1; IG: 10.8; Unknown: CG: 6.4; IG: 1.2; - Pre-pregnancy BMI: CG: 23.3±3.9; IG: 22.8±3.4; - FBG <92 mg/dl (%): 100; - Current GDM (%): CG: 20.4; IG: 13.6, p=0.042; - Smoking (%): Current: CG: 2.4; IG: 2 | CG vs IG; FFQ at: 8-12 GW, 24-28 GW, 36-38 GW; DP Description:; - Both groups: MedDiet (vegetables, fruits, skimmed dairy foods, whole grain cereals, legumes, fish; avoid refined grains, baked goods, soft drinks, juices, junk food, precooked meat, pre-sliced slices of bread) and walking 30 min/d recommended; - Intervention group (IG): Recommended to consume ≥40 ml/d EVOO and 25-30 g/d roasted pistachios recommended; Weekly visits with a dietitian; - Control group (CG): Recommended to restrict dietary fat, including extra virgin coconut oil and dry fruits, by the midwives.; Adherence: MEDAS scores did not differ at baseline. Scores significantly increased over time in both groups, but the IG had significantly higher scores than the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcome and assessment methods:; BP assessed at 24-28 GW and 36-38 GW; Gestational HTN, PE, and Proteinuria assessed at: >20 GW; Gestational HTN and PE recorded as pre-delivery outcomes. BP monitored after participants sat for ≥10 min.; [underlined: Gestational HTN]: Systolic BP ≥140 mm Hg and diastolic BP ≥90 mm Hg; [underlined: PE:] Gestational HTN w/ proteinuria (>300mg in 24h) | Systolic BP; Student t test; Mean±SD, mmHg; [underlined: 24-28 GW:] IG: 110±13; CG: 100±14, p=1.00; [underlined: 36-38 GW:] IG: 114±18; CG: 115±16, p=0.512; Diastolic BP; Student t test; Mean±SD, mmHg; [underlined: 24-28 GW:] IG: 61±9; CG: 60±8, p=0.189; [underlined: 36-38 GW:] IG: 74±7; CG: 74±6, p=1.00; Gestational Hypertension Chi-squared test, %; IG: 2.4; CG: 3.6, p=0.431; Preeclampsia; Chi-squared test, %; IG: 1.6; CG: 2.0, p=0.736 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP,; Funding: None; Summary: A MedDiet with recommended additional EVOO and pistachios had no effect on blood pressure at 24-28 GW or 36-38 GW, gestational hypertension, or preeclampsia.
NRCT
Melero, 2020^30^; NRCT, Spain, St. Carlos GDM prevention study; Baseline N=600; Analytic N= 416 (Attrition: 9%); - Age (y): CG: 31.3±5.6; RW: 31.4±5.7; - Race/Ethnicity (%): Hispanic: 100; - SEP:; ○ Education (%): Elementary: CG: 19.7; RW: 11.2; Secondary: CG: 47.2; RW: 50.8; University: CG: 31.7; RW: 35.5; Unknown: CG: 1.4; RW: 2.5; ○ Unemployed (%): CG: 69.0; RW: 73.3; - Pre-pregnancy BMI: CG: 24.4±4.0; RW: 23.4±3.6, p=0.033; - Current GDM (%): CG: 25.8; RW: 13.4, p=0.011; - Smoking (%): CG: 0.7; RW: 1.6 | RW vs CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg legumes/wk, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between the groups at baseline. Scores significantly increased over time in the IG, while no changes in the CG were observed. Scores remaining significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; - Negative components: commercial pastries; red meat or sausages; animal fat; sugar-sweetened beverages; - Alcohol and fruit (including juice) component excluded; Outcome and assessment methods:; BP assessed at: 24-28 GW and 36-38 GW;; Gestational HTN, PE, and Proteinuria assessed at: >20 GW; BP assessed while sitting after resting for 10 min.; [underlined: Gestational HTN:] >140 mmHg SBP or >90 mmHg DBP; [underlined: PE:] Gestational HTN w/ proteinuria (>300 mg in 24h); [underlined: Proteinuria:] >300 mg in 24h w/o gestational HTN | Systolic BP; Student t test or Mann-Whitney U test if normal distribution; Shapiro-Wilk test if not-normal distribution; Mean±SD, mmHg; [underlined: 24-28 GW:] CG: 104±11; RW: 105±11, p=0.164; [underlined: 36-38 GW:] CG: 115±16; RW: 115±14, p=0.256; Diastolic BP; Student t test or Mann-Whitney U test if normal distribution; Shapiro-Wilk test if not-normal distribution; Mean±SD, mmHg; [underlined: 24-28 GW:] CG: 63±9; RW: 63±9, p=0.413; [underlined: 36-38 GW:] CG: 72±9; RW: 71±10, p=0.589; Gestational Hypertension Chi-squared test, %; CG: 6.1; RW: 2.1, p=0.05; Preeclampsia; Chi-squared test, %; CG: 4.5; RW: 1.4, p=0.245; Proteinuria; Chi-squared test, %; CG: 2.3; RW: 0.0, p=0.037 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Among Hispanic participants, a MedDiet in a real-world (RW) setting was associated with lower incidence of proteinuria and the association neared significance for lower incidence of gestational hypertension. RW did not have an effect on systolic or diastolic blood pressure at 24-28 GW or 36-38 GW or preeclampsia, compared to CG.
Cohort Studies
Index/Score
Arvizu, 2020^1^; PCS, Denmark, DNBC Analytic N =66,651; - Age at birth (y):; ○ AHA primary: Quintile 1: 29±4; Quintile 5: 31±4, p<0.05; ○ AHA secondary: Quintile 1: 29±4; Quintile 5: 31±4, p<0.05; ○ DASH: Quintile 1: 30±4; Quintile 5: 31±4, p<0.05; - ≥High school graduate (%):; ○ AHA primary: Quintile 1: 32; Quintile 5: 48, p<0.05; ○ AHA secondary: Quintile 1: 30; Quintile 5: 50, p<0.05; ○ DASH: Quintile 1: 33; Quintile 5: 47, p<0.05; - Pre-pregnancy BMI:; ○ AHA primary: Quintile 1: 24.3±4.69; Quintile 5: 22.8±3.66, p<0.05; ○ AHA secondary: Quintile 1: 24.2±4.65; Quintile 5: 22.9±3.65, p<0.05; ○ DASH: Quintile 1: 24.4±4.66; Quintile 5: 22.7±43.61, p<0.05; - History of HDP (%): 0.0; - Never smoked (%):; ○ AHA primary: Quintile 1: 67; Quintile 5: 82, p<0.05; ○ AHA secondary: Quintile 1: 65; Quintile 5: 84, p<0.05; ○ DASH: Quintile 1: 68; Quintile 5: 81, p<0.05 | AHA Primary, AHA Secondary, & DASH (quintiles of alignment); FFQ at: ~25 GW; DP Descriptions:; [underlined: AHA Primary]; - Positive components: Fruits and vegetables; Whole grains; Fish and shellfish; - Negative components: SSB; Sodium; [underlined: AHA Secondary]; - Positive components: Fruits and vegetables; Whole grains; Fish and shellfish; Nuts, seeds, and legumes; - Negative components: SSB; Sodium; Processed meat; Saturated fat; [underlined: DASH]; - Positive components: Fruits and juices; Vegetables; Nuts/legumes; Whole grains; Low-fat dairy; - Negative components: Red/processed meat; SSB; Sodium; Outcome and assessment methods:; PE and Gestational HTN assessed at: NR; Diagnoses obtained via linkage to the Danish National Patient Registry. Outcomes defined following International Classification of Diseases-10 codes; Total PE includes severe PE. | Total Preeclampsia; Log-Poisson regression; RR (95% CI); [underlined: AHA Primary (Quintiles)]; 2 vs. 1 (Ref): 1.08 (0.92, 1.27), p≥0.05; 3 vs. 1 (Ref): 1.01 (0.86, 1.18), p≥0.05; 4 vs. 1 (Ref): 0.92 (0.77, 1.10), p≥0.05; 5 vs. 1 (Ref): 0.90 (0.75, 1.08), p≥0.05; p for trend=0.13; [underlined: AHA Secondary (Quintiles)]; 2 vs. 1 (Ref): 0.95 (0.81, 1.12), p≥0.05; 3 vs. 1 (Ref): 0.90 (0.75, 1.08), p≥0.05; 4 vs. 1 (Ref): 1.02 (0.86, 1.22), p≥0.05; 5 vs. 1 (Ref): 0.95 (0.79, 1.14), p≥0.05; p for trend=0.78; [underlined: DASH (Quintiles)]; 2 vs. 1 (Ref): 0.99 (0.83, 1.19), p≥0.05; 3 vs. 1 (Ref): 1.02 (0.87, 1.20), p≥0.05; 4 vs. 1 (Ref): 0.93 (0.77, 1.12), p≥0.05; 5 vs. 1 (Ref): 0.96 (0.80, 1.15), p≥0.05; p for trend=0.57; Subgroup analyses where participants with gestational HTN or pre-pregnancy chronic HTN were excluded, respectively, did not substantively alter the results; Severe Preeclampsia; Log-Poisson regression; RR (95% CI); [underlined: AHA Primary (Quintiles)]; 2 vs. 1 (Ref): 0.81 (0.56, 1.17), p≥0.05; 3 vs. 1 (Ref): 0.99 (0.70, 1.40) , p≥0.05; 4 vs. 1 (Ref): 0.92 (0.64, 1.33), p≥0.05; 5 vs. 1 (Ref): 1.07 (0.74, 1.55), p≥0.05; p for trend=0.69; [underlined: DASH (Quintiles)]; 2 vs. 1 (Ref): 1.05 (0.73, 1.51), p≥0.05; 3 vs. 1 (Ref): 0.89 (0.64, 1.25), p≥0.05; 4 vs. 1 (Ref): 0.96 (0.64, 1.44), p≥0.05; 5 vs. 1 (Ref): 1.12 (0.77, 1.63), p≥0.05; Gestational Hypertension; Log-Poisson regression; RR (95% CI); [underlined: AHA Primary (Quintiles)]; 2 vs. 1 (Ref): 0.92 (0.69, 1.23), p≥0.05; 3 vs. 1 (Ref): 1.08 (0.82, 1.41), p≥0.05; 4 vs. 1 (Ref): 0.95 (0.71, 1.28), p≥0.05; 5 vs. 1 (Ref): 1.20 (0.90, 1.60), p≥0.05; p for trend=0.26; [underlined: DASH (Quintiles)]; 2 vs. 1 (Ref): 0.85 (0.63, 1.15), p≥0.05; 3 vs. 1 (Ref): 0.92 (0.74, 1.19), p≥0.05; 4 vs. 1 (Ref): 1.07 (0.80, 1.44), p≥0.05; 5 vs. 1 (Ref): 0.99 (0.74, 1.33), p≥0.05; p for trend=0.80; Subgroup analyses where participants with preeclampsia were excluded did not substantively alter the results | Key confounders accounted for: Age, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: TEI, Height, Vitamin C intake, Vitamin E intake; Funding: March of Dimes Foundation; the European Union; Danish National Research Foundation; Danish Health Foundation; Danish Heart Foundation; NIH; Summary: Alignment with the AHA Primary DP, AHA Secondary DP, and DASH DP was not associated with risk of total preeclampsia, severe preeclampsia, or gestational hypertension.
Courtney, 2020^3^; PCS, Ireland, ROLO; Analytic N =465; - Age (y): 32.2±4.0; - Race/Ethnicity (%): White: 97.7; Other: 2.3; - SEP:; ○ Education (%): <3rd level: 42.8; - Early pregnancy BMI (%): 25-29.9: 38.1; ≥30: 16.5; - Current GDM (%): 2.2; - Current T1 or T2 DM (%): 0.0; - Smoking (%): 2.7 | Modified DASH (continuous alignment); Food Diary at: TM1, TM2, and TM3; DP Description:; - Positive components: fruit and fruit juice; vegetables; whole grains; nuts/seeds/legumes; low-fat dairy; - Negative components: red lean/red processed meat; SSB, sweet snacks, and desserts; sodium; salty snacks; Outcome and assessment methods:; BP assessed at: 28 GW and 34 GW; Systolic BP and Diastolic BP measured by the doctors and/or midwife at rest.; MAP calculated as [DBP + 1/3 x (SBP − DBP)] | Systolic BP; Multiple linear regression; β (95% CI) per increase in DASH score; [underlined: TM2:] −0.169 (−0.961, 0.622), p=0.675; [underlined: TM3:] −0.268 (−0.987, 0.451), p=0.465; Multiple linear regression; β per 5-unit increase in DASH score; [underlined: TM2:] 0.005, p=0.990; [underlined: TM3:] −0.330, p=0.471; Diastolic BP; Multiple linear regression; β (95% CI) per increase in DASH score; [underlined: TM2:] −0.439 (−0.953, 0.075), p=0.094; [underlined: TM3:] −0.680 (−1.194, −0.166), p=0.010; Multiple linear regression; β per 5-unit increase in DASH score; [underlined: TM2:] −0.385, p=0.236; [underlined: TM3:] −0.755, p=0.022; Mean Arterial Pressure; Multiple linear regression; β (95% CI) per increase in DASH score; [underlined: TM2:] −0.349 (−0.883, 0.184), p=0.199; [underlined: TM3:] −0.543 (−1.043, −0.043), p=0.033; Multiple linear regression; β per 5-unit increase in DASH score; [underlined: TM2:] −0.255, p=0.451; [underlined: TM3:] −0.615, p=0.055 | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI,; Other covariates: Trial group; TEI; Funding: Health Research Centre for Health and Diet Research; National Maternity Hospital Medical Fund; Summary: Greater alignment with DASH was associated with lower third trimester, but not second trimester, diastolic blood pressure and mean arterial pressure. Alignment with DASH was not associated with second or third trimester systolic blood pressure.
Ding, 2021^5^; PCS, China, Tongji MCHC; Analytic N =1,489; - Age (y): Q1: 28.3±3.5; Q4 28.6±3.5; - SEP:; ○ Education (%): ≤9y: Q1: 4.2; Q4: 1.4; ≥16y: Q1: 50.6; Q4: 67.7, p<0.01; ○ Household income (%): ≤1000 Yuan/mo: Q1: 1.2; Q4: 0.2; ≥10,000 Yuan/mo: Q1: 12.7; Q4: 22.8, p<0.01; - Pre-pregnancy BMI: Q1: 21.1±2.9; Q4: 20.7±2.5 | CDGCI-PW (continuous alignment); FFQ at: 16-20 GW; DP Description:; - Positive components: staple foods (cereals and their products, potatoes, and beans other than soybeans); green leafy and colored vegetables (red and yellow); milk and its products (milk, yogurt, formula milk powder); soybean and its products; nuts; lean meat (livestock and poultry meat); animal blood and liver; iodized table salt, iodine-rich seafood; - Negative components: pickled food, fried food, cream cake, chocolate, other high-salt, high-oil, and high-sugar food; [underlined: Outcome and assessment methods:]; Gestational HTN assessed at: each study visit ≥20 GW; Gestational HTN: Diagnosed if BP ≥140/90 mmHg | Gestational Hypertension; Multivariable logistic regression; OR (95% CI) per 10 pt score increase; 0.30 (0.20,0.37), p<0.01; Alternately excluding one component of the CDGCI-PW score did not substantively change the association | Key confounders accounted for: Age, SEP, Pre-pregnancy BMI, Parity,; Other covariates: GWG in TM2; Funding: National Program on Basic Research Project of China; The Fundamental Research Funds for the Central Universities; Summary: Greater alignment with the CDGCI-PW was associated with lower risk of gestational HTN.
Flor-Alemany, 2021^6^; PCS, Spain, GESTAFIT Analytic N =107; - Age (y): 33.2±4.4; - SEP:; - Education (%): Low: 10.9; High: 58.8; - Pre-pregnancy BMI: (%) 25-<30: 25.2; ≥30: 10.1; - Fasting glucose (mg/dL): 77.4±15.9; - Smoking (%): Current: 8.4; Former: 37.0 | MedDietScore (continuous alignment); FFQ at: 16 GW; DP Description:; - Positive components: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil.; - Negative components: Red and Processed Meat; Poultry; Full-Fat Dairy; - Alcohol component excluded; Outcome and assessment methods:; BP assessed at: 34 GW; Systolic BP and Diastolic BP measured after 5 min rest on 2 separate occasions (w/ 2 min btw trials). Lowest value selected for analysis. | Systolic BP; Linear regression; β, mmHg; -0.260, p=0.007; Diastolic BP; Linear regression; β, mmHg; -0.198, p=0.044 | Key confounders accounted for: Age, Physical activity, SEP, Pre-pregnancy BMI, Smoking, DM in current pregnancy; Funding: Regional Ministry of Health of the Junta de Andalucía; University of Granada, Unit of Excellence on Exercise and Health (UCEES); Spanish Ministry of Education, Culture and Sports; Summary: Grater alignment with the MedDietScore at 16 GW was associated with lower SBP and DBP at 34 GW.
Fulay, 2018^7^; PCS, United States, Project Viva; Analytic N =1,719; - Age (y): 32.2±4.9; - Race/Ethnicity (%): White: 71.9; Black: 12.3; Hispanic: 6.5; Asian: 5.6; Other: 3.6; - SEP:; ○ Household income (%): <$20,000/y: 3.1; >$70,000/y: 60.1; ○ Education (%): Primary: 9.4; ≥College: 32.0; - Pre-pregnancy BMI (%): 25-<30: 21.7; ≥30: 12.9; - Previous HTN (%): 4.5; - Current GDM (%): 5.2; - T1 or T2 DM (%): 0.0; - Smoking (%): 10.9 | DASH & DASH OMNI (continuous alignment); FFQ at: ~11 GW; DP Description:; [underlined: DASH]; - Positive components: fruits; vegetables; whole grains; nuts/legumes; low-fat dairy; - Negative components: sodium; SSB; red and/or processed meats; [underlined: DASH OMNI]; - Positive components: fruits; vegetables; whole grains; nuts/legumes; low-fat dairy; MUFA and PUFA; - Negative components: sodium; SSB; red and/or processed meats; Outcome and assessment methods:; BP assessed at: 36 GW; HDP assessed at: >20 GW; Outcomes taken from outpatient charts.; [underlined: HDP:] Gestational HTN or PE; Gestational HTN: SBP >140 mmHg or DBP >90 mmHg ≥2x; [underlined: PE:] Gestational HTN and proteinuria (dipstick 1+ ≥2x or ≥2 once) >4h but ≤7d apart, or chronic HTN and proteinuria | Systolic BP; Linear regression; β (95% CI), mmHg; [underlined: DASH:] 0.07 (−0.04, 0.19), p≥0.05; [underlined: DASH OMNI:] 0.05 (−0.06, 0.17), p≥0.05; Diastolic BP; Linear regression; β (95% CI), mmHg; [underlined: DASH:] 0.05 (−0.04, 0.14), p≥0.05; [underlined: DASH OMNI:] 0.05 (−0.04, 0.14), p≥0.05; Hypertensive Disorders of Pregnancy; Logistic regression; OR (95% CI); [underlined: DASH:] 1.00 (0.96, 1.03), p≥0.05; [underlined: DASH OMNI:] 0.99 (0.96, 1.03), p≥0.05; Additionally adjusting for Western and Prudent dietary patterns did not substantially alter the results | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: GWG until FFQ; TEI; Funding: NIH; Summary: Alignment with DASH or DASH OMNI was not associated with systolic or diastolic blood pressure or risk of hypertensive disorders of pregnancy.
Hillesund, 2014^10^; PCS, Norway, MoBa; Analytic N =72,072; - Age (y): 30.1±4.6; ○ ≥35 (%): 12.2; - Race/Ethnicity (%): White: >99; - SEP:; ○ Education (%): ≤12y: 31.1; ≥17y: 25.3; - Pre-pregnancy BMI (%): 25-29.9: 21.1; 30-34.9: 6.7; ≥35: 2.5; - T1 or T2 DM (%): 0.6; - Current GDM (%): 0.9; - Smoking (%): Occasional: 2.7; Daily: 5.2 | NND (categorical alignment); FFQ at: 20.7±3.7 GW; DP Description:; - Positive components: meal frequency; Nordic fruits (apples, pears, plums, and strawberries); root vegetables; cabbages; potatoes:total potatoes, rice, or pasta; whole grain bread over refined bread; oatmeal; foods from the wild countryside (wild fish, seafood, game, and wild berries); milk over juice; water:SSB; Outcome and assessment methods:; Total PE assessed at: >20 GW; Early PE assessed at: >20 GW to <34 GW; [underlined: Total PE:] Reported preeclampsia (>140 mmHg SBP or >90 mmHg DBP w/ proteinuria (protein excretion ≥0.3 g/24h or >1+ on dip-stick assay), both measured ≥2x), eclampsia, HELLP syndrome (hemolysis, elevated liver enzymes, and low platelet count), or preeclampsia superimposed on chronic HTN on the birth notification form; [underlined: Early PE:] PE diagnosed <34 GW | Total Preeclampsia; Logistic regression; OR (95% CI); [underlined: All participants]; Medium vs. Low (Ref): 0.91 (0.83, 1.00); High vs. Low (Ref): 0.86 (0.78, 0.95); [underlined: Smoking participants]; Medium vs. Low (Ref): 0.63 (0.44, 0.90); High vs. Low (Ref): 0.57 (0.37, 0.87); [underlined: Non-smoking participants]; Medium vs. Low (Ref): 0.94 (0.85, 1.04); High vs. Low (Ref): 0.88 (0.80, 0.98); [underlined: Participants with T1 or T2 DM]; High vs. Low (Ref): 0.38 (0.15, 0.95); [underlined: Participants with GDM]; High vs. Low (Ref): 0.86 (0.36, 2.0); Early Preeclampsia; Logistic regression; OR (95% CI); [underlined: All participants]; Medium vs. Low (Ref): 0.84 (0.63, 1.12); High vs. Low (Ref): 0.71 (0.52, 0.96); Removing participants w/ DM or chronic HTN did not substantively change the results; Stronger associations were generally observed among nulliparous participants and participants w/ BMI <30, whereas weaker or non-significant associations were observed among multiparous participants and participants w/ BMI ≥30 (data not shown) | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: TEI; Funding: Norwegian Ministry of Health; Norwegian Ministry of Education and Research; NIH/NIEHS; NIH/NINDS; Norwegian Research Council/FUGE; University of Agder; Summary: Greater alignment with the NND was associated with reduced risk of total preeclampsia in all participants, participants who smoked during pregnancy, participants who didn’t smoke during pregnancy, and participants with T1 or T2 DM. Alignment with the NND was not associated with reduced risk of preeclampsia in participants with GDM. Greater alignment with the NND was associated with reduced risk of early preeclampsia. Stronger associations were generally observed among nulliparous participants and participants w/ BMI <30, whereas weaker or non-significant associations were observed among multiparous participants and participants w/ BMI ≥30.
Hillesund, 2018^11^; PCS, Norway, NFFD; Analytic N =582; - Age (y): 28.0±4.4; ○ (%): ≥35: 6.8; - Race/Ethnicity (%): “Predominantly White”; - SEP:; ○ Education (%): ≤12y: 31.8; ≥16y: 35.5; ○ Occupation (%): Work outside home: 84.2; Student: 8.7; Unemployed: 3.9; Sick leave/disabled: 1.9; Homemaker: 1.4; ○ Income (%): ≤400,000 NOK: 31.2; >700,000 NOK: 34.4; NR: 6.6; - Pre-pregnancy BMI (%): 25-29.9: 20.2; ≥30: 7.6; - Pre-existing DM (%): 0.0; - Current GDM (%): 9.1; - Smoking (%): 3.9 | NFFD diet (continuous alignment); FFQ at: ~15 GW; DP Description:; - Positive components: regular meals; drinking water when thirsty; vegetables w/ dinner; fruits and vegetables btw meals; reading nutrition labels before buying; - Negative components: sweets and snacks without appreciation; large portion sizes of unhealthy foods; added sugar; salt; eating beyond satiety; Outcome and assessment methods:; PE assessed at: >20 GW; Severe PE/HELLP/Eclampsia assessed at: >20 to <34 GW; [underlined: PE]: SP ≥140 mmHg or DP ≥90 mmHg plus proteinuria (protein excretion ≥0.3 g/24 h or ≥1+ on dipstick), both measured ≥2x; [underlined: Severe PE/HELLP/Eclampsia:] PE <34 GW and/or severity of symptoms, obtained from hospital charts. HELLP/eclampsia defined as PE affecting hemolysis, liver function, and platelet counts. | Total Preeclampsia; Multivariate logistic regression; OR (95% CI) per 1 pt score increase; 0.90 (0.73, 1.10), p=0.325; Severe Preeclampsia/HELLP/Eclampsia; Multivariate logistic regression; OR (95% CI); 0.90 (0.67, 1.17), p=0.429; Sensitivity analysis confined to the control group in the original trial did not materially impact the results | Key confounders accounted for: Age, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: Marital status, Randomization assignment
Hillesund, 2018^11^ cont.; Analytic N=472 | | Total Preeclampsia; Multivariate logistic regression; OR (95% CI); 0.78 (0.62, 0.99), p=0.038; Severe Preeclampsia/HELLP/Eclampsia; Multivariate logistic regression; OR (95% CI); 0.74 (0.54, 1.01), p=0.060; Sensitivity analysis confined to the control group in the original trial resulted in non-significant findings for total PE, but did not materially impact the results of Severe PE/HELLP/Eclampsia | Key confounders accounted for: Age, Physical activity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: Marital status; Randomization assignment; Funding: South-Eastern Norway Regional Health Authority; Municipalities of southern Norway; University of Agder; Summary: When additionally controlling for physical activity, greater alignment with the Norwegian Fit for Delivery diet score in early pregnancy was significantly associated with a reduced risk of total preeclampsia, and was nearly significantly associated with a reduced risk of severe preeclampsia/HELLP/eclampsia. When confined to the control group in the original trial, findings for risk of total preeclampsia were no longer significant.
Li, 2021^14^; PCS, United States, NICHD Fetal Growth Studies–Singletons; Analytic N =Gestational HTN: 8-13 GW: 1,505; 16-22 GW: 1,682; 24-29 GW: 1,652; PE: 8-13 GW: 1,502; 16-22 GW: 1,685; 24-29 GW: 1,649; - Age (y):; ○ AHEI: Q1: 25.9±5.57; Q4: 30.5±4.84, p<0.001; ○ aMED: Q1: 26.4±5.70; Q4: 29.9±5.29, p<0.001; ○ DASH: Q1: 25.5±5.43; Q4: 30.4±4.84, p<0.001; - Race/Ethnicity (%):; - AHEI: NHB: Q1: 49.1; Q4: 14.9; Hispanic: Q1: 24.1; Q4: 26.2; NHW: Q1: 17.9; Q4: 27.5; AAPI: Q1: 8.9; Q4: 31.4, p<0.001; ○ aMED: NHB: Q1: 39.9; Q4: 22.4; Hispanic: Q1: 28.7; Q4: 25.4; NHW: Q1: 20.5; Q4: 26.0; AAPI: Q1: 11.0; Q4: 26.3, p<0.001; ○ DASH: NHB: Q1: 55.3; Q4: 14.0; Hispanic: Q1: 21.5; Q4: 29.2; NHW: Q1: 10.1; Q4: 37.5; AAPI: Q1: 13.1; Q4: 19.3, p<0.001; - Education (%):; ○ AHEI: <High school: Q1: 12.2; Q4: 9.4; High school/equivalent: Q1: 27.5; Q4: 12.4; Graduate degree: Q1: 6.9; Q4: 28.7, p<0.001;; ○ aMED: <High school: Q1: 14.6; Q4: 8.3; High school/equivalent: Q1: 27.8; Q4: 12.4; Graduate degree: Q1: 9.0; Q4: 26.0, p<0.001;; ○ DASH: <High school: Q1: 14.8; Q4: 8.5; High school/equivalent: Q1: 31.0; Q4: 10.5; Graduate degree: Q1: 5.6; Q4: 30.6, p<0.001; - Pre-pregnancy BMI: (%):; ○ AHEI: 25-29: Q1: 29.8; Q4: 21.3; ≥30: Q1: 20.3; Q4: 11.4, p<0.001; ○ aMED: 25-29: Q1: 30.1; Q4: 22.4; ≥30: Q1: 21.3; Q4: 9.7, p<0.001; ○ DASH: 25-29: Q1: 29.6; Q4: 25.1; ≥30: Q1: 19.0; Q4: 11.6, p=0.01; - Current DM (%): 0.0; - History of severe PE if pre-pregnancy BMI <30: 0.0; - Smoking (%): Pre-pregnancy BMI <30: 0.0 | AHEI, aMED, & DASH (quartiles of alignment); FFQ at: 8-13 GW; 24h recall at 16-22 GW, 24-29 GW; DP Descriptions:; [underlined: AHEI]; - Positive components: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA; - Negative components: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Sodium; - Alcohol and trans-fat components excluded; [underlined: aMED]; - Positive components: Vegetables; Fruit; Nuts; Fish; Lean Meat (poultry, lean beef); - Negative components: Red and Processed Meat; Sodium. Neutral: Grains and Starches; Dairy Foods; - Alcohol component excluded; [underlined: DASH]; - Positive components: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; - Negative components: Red and Processed Meat; Sweetened Beverages; Sodium; Outcome and assessment methods:; PE and Gestational HTN assessed at: >20 GW; Outcomes extracted from postpartum discharge diagnosis.; [underlined: Gestational HTN:] unspecified and new onset HTN, defined as SBP ≥140 mmHg or DBP ≥90 mmHg w/o proteinuria.; [underlined: PE:] New onset of HTN w/ proteinuria (≥0.3g protein in 24h urine). Mild & severe PE, HELLP syndrome, and eclampsia included within PE.; Comparison group for both gestational HTN and PE was participants w/o either diagnosis. | Gestational Hypertension; Log-binomial regression; RR (95% CI); [underlined: AHEI]; 8-13 GW; Q2 vs. Q1 (Ref): 0.59 (0.30, 1.15), p≥0.05; Q3 vs. Q1 (Ref): 0.71 (0.35, 1.46), p≥0.05; Q4 vs. Q1 (Ref): 0.38 (0.14, 1.04), p≥0.05; p for trend=0.06; 16-22 GW; Q2 vs. Q1 (Ref): 0.91 (0.47, 1.79), p≥0.05; Q3 vs. Q1 (Ref): 0.91 (0.46, 1.82), p≥0.05; Q4 vs. Q1 (Ref): 0.77 (0.34, 1.72), p≥0.05; p for trend=0.54; 24-29 GW; Q2 vs. Q1 (Ref): 0.92 (0.49, 1.71), p≥0.05; Q3 vs. Q1 (Ref): 0.48 (0.21, 1.06), p≥0.05; Q4 vs. Q1 (Ref): 0.80 (0.36, 1.77), p≥0.05; p for trend=0.27; [underlined: aMED]; 8-13 GW; Q2 vs. Q1 (Ref): 0.86 (0.47, 1.59), p≥0.05; Q3 vs. Q1 (Ref): 0.40 (0.14, 1.12), p≥0.05; Q4 vs. Q1 (Ref): 0.47 (0.18, 1.28), p≥0.05; p for trend=0.08; 16-22 GW; Q2 vs. Q1 (Ref): 1.13 (0.60, 2.10), p≥0.05; Q3 vs. Q1 (Ref): 0.81 (0.39, 1.70), p≥0.05; Q4 vs. Q1 (Ref): 0.71 (0.31, 1.61), p≥0.05; p for trend=0.32; 24-29 GW; Q2 vs. Q1 (Ref): 1.03 (0.52, 2.03), p≥0.05; Q3 vs. Q1 (Ref): 1.12 (0.55, 2.27), p≥0.05; Q4 vs. Q1 (Ref): 1.09 (0.51, 2.35), p≥0.05; p for trend=0.77; [underlined: DASH]; 8-13 GW; Q2 vs. Q1 (Ref): 0.91 (0.51, 1.60), p≥0.05; Q3 vs. Q1 (Ref): 0.33 (0.12, 0.88), p<0.05; Q4 vs. Q1 (Ref): 0.45 (0.17, 1.17), p≥0.05; p for trend=0.04; 16-22 GW; Q2 vs. Q1 (Ref): 0.82 (0.43, 1.56), p≥0.05; Q3 vs. Q1 (Ref): 0.79 (0.40, 1.58), p≥0.05; Q4 vs. Q1 (Ref): 0.19 (0.05, 0.65), p<0.05; p for trend=0.01; 24-29 GW; Q2 vs. Q1 (Ref): 0.97 (0.50, 1.86), p≥0.05; Q3 vs. Q1 (Ref): 1.06 (0.49, 2.29), p≥0.05; Q4 vs. Q1 (Ref): 0.82 (0.34, 1.96), p≥0.05; p for trend=0.75; Preeclampsia; Log-binomial regression; RR (95% CI); [underlined: AHEI]; 8-13 GW; Q2 vs. Q1 (Ref): 1.24 (0.61, 2.51), p≥0.05; Q3 vs. Q1 (Ref): 1.14 (0.53, 2.43), p≥0.05; Q4 vs. Q1 (Ref): 0.77 (0.30, 2.00), p≥0.05; p for trend=0.71; 16-22 GW; Q2 vs. Q1 (Ref): 0.83 (0.43, 1.60), p≥0.05; Q3 vs. Q1 (Ref): 1.22 (0.66, 2.24), p≥0.05; Q4 vs. Q1 (Ref): 0.26 (0.09, 0.78), p<0.05; p for trend=0.07; 24-29 GW; Q2 vs. Q1 (Ref): 0.85 (0.44, 1.63), p≥0.05; Q3 vs. Q1 (Ref): 0.69 (0.34, 1.41), p≥0.05; Q4 vs. Q1 (Ref): 0.31 (0.11, 0.87), p<0.05; p for trend=0.03; [underlined: aMED]; 8-13 GW; Q2 vs. Q1 (Ref): 1.09 (0.54, 2.21), p≥0.05; Q3 vs. Q1 (Ref): 0.93 (0.38, 2.30), p≥0.05; Q4 vs. Q1 (Ref): 0.68 (0.25, 1.85), p≥0.05; p for trend=0.53; 16-22 GW; Q2 vs. Q1 (Ref): 0.30 (0.13, 0.69), p<0.05; Q3 vs. Q1 (Ref): 0.77 (0.41, 1.45), p≥0.05; Q4 vs. Q1 (Ref): 0.67 (0.34, 1.32), p≥0.05; p for trend=0.43; 24-29 GW; Q2 vs. Q1 (Ref): 0.91 (0.47, 1.75), p≥0.05; Q3 vs. Q1 (Ref): 1.02 (0.51, 2.04), p≥0.05; Q4 vs. Q1 (Ref): 0.47 (0.18, 1.21), p≥0.05; p for trend=0.22; [underlined: DASH]; 8-13 GW; Q2 vs. Q1 (Ref): 0.99 (0.49, 2.02), p≥0.05; Q3 vs. Q1 (Ref): 1.27 (0.59, 2.74), p≥0.05; Q4 vs. Q1 (Ref): 0.72 (0.28, 1.89), p≥0.05; p for trend=0.75; 16-22 GW; Q2 vs. Q1 (Ref): 0.77 (0.41, 1.45), p≥0.05; Q3 vs. Q1 (Ref): 0.33 (0.13, 0.83), p<0.05; Q4 vs. Q1 (Ref): 0.94 (0.45, 1.96), p≥0.05; p for trend=0.50; 24-29 GW; Q2 vs. Q1 (Ref): 0.70 (0.35, 1.41), p≥0.05; Q3 vs. Q1 (Ref): 0.82 (0.39, 1.73), p≥0.05; Q4 vs. Q1 (Ref): 0.56 (0.23, 1.38), p≥0.05; p for trend=0.25 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: Marital status; Family history of DM; Sleep duration; TEI; Funding: NICHD; AARA; Summary: Greater alignment with the DASH at 8-13 GW and 16-22 GW, but not 24-29 GW, was associated with reduced risk of gestational hypertension. All associations between aMED and AHEI and gestational hypertension were non-significant, but alignment with both at 8-13 GW neared statistical significance for reduced risk of gestational hypertension.; Greater alignment with the AHEI at 24–29 GW, but not 8-13 GW or 16-22 GW, was associated with reduced risk of preeclampsia. The second quartile of alignment with aMED at 16-22 GW was associated with reduced risk of preeclampsia compared to the lowest quartile, but all other associations between aMED and preeclampsia were non-significant. The third quartile of alignment with DASH at 16-22 GW was associated with reduced risk of preeclampsia compared to the lowest quartile, but all other associations between DASH and risk of preeclampsia were non-significant.
Makarem, 2022^16^; PCS, United States, nuMoM2b; Analytic N =7,798; - Age (y): 27.4±5.5; ○ (%): ≥35: 9.7; - Race/Ethnicity (%): NHW: 63.9; Hispanic: 16.6; NHB: 10.5; Asian: 4.3; Other: 4.6; - SEP:; - Education (%): <High school: 5.7; ≥Bachelor’s: 55.6; - Baseline BMI ≥30 (%): 19.5; - History of HDP (%): 100% nulliparous; - Current GDM (%): 3.8; - Smoking (%): Ever: 41.4 | aMED (categorical alignment, quintiles of alignment); FFQ at: 6-<14 GW; DP Description:; - Positive components: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA:SFA; - Moderate component: Alcohol; - Negative component: Red and Processed Meat; Outcome and assessment methods:; PE or Eclampsia and Gestational HTN assessed at: >20 GW; [underlined: Gestational HTN]: New onset SBP ≥140mmHg or DBP ≥90mmHg twice ≥4h apart; [underlined: PE:] Gestational HTN w/ proteinuria (≥0.3 g protein in 24h urine); [underlined: Eclampsia:] New-onset tonic-clonic, focal, or multifocal seizures in the absence of other causative conditions | Preeclampsia or Eclampsia; Multivariable logistic regression; OR (95% CI); [underlined: Categorical]; Moderate vs. Low (Ref): 0.85 (0.68, 1.07), p=0.17; High vs. Low (Ref): 0.72 (0.55, 0.93) p=0.01; [underlined: Quintiles]; 2 vs. 1 (Ref): 0.93 (0.73, 1.18), p=0.54; 3 vs. 1 (Ref): 0.61 (0.44, 0.86), p=0.005; 4 vs. 1 (Ref): 0.67 (0.48, 0.94), p=0.02; 5 vs. 1 (Ref): 0.65 (0.46, 0.92), p=0.02; p for trend=0.01; Gestational Hypertension; Multivariable logistic regression; OR (95% CI); [underlined: Categorical]; Moderate vs. Low (Ref): 0.89 (0.74, 1.07), p=0.21; High vs. Low (Ref): 0.85 (0.70, 1.03), p=0.11; [underlined: Quintiles]; 2 vs. 1 (Ref): 0.98 (0.81, 1.19), p=0.82; 3 vs. 1 (Ref): 0.90 (0.70, 1.15), p=0.41; 4 vs. 1 (Ref): 0.85 (0.66, 1.10), p=0.23; 5 vs. 1 (Ref): 0.89 (0.69, 1.15), p=0.36; p for trend=0.77 | Key confounders accounted for: Age, Race/ethnicity, SEP, Prep-regnancy BMI, Smoking, Parity, History of HDP,; Other covariates: Marital status; Family history of CVD; Funding: NIH/ORWH BIRCWH; NIH/NHLBI; NIH/NICHD; OBSSR; NCATS; NIH/NIA; the Barbra Streisand Women’s Cardiovascular Research and Education Program; the Erika J. Glazer Women’s Heart Research Initiative; AHA; NIH/NINDS; the Gerstner Family Foundation; Summary: Greater alignment with the aMED was associated with reduced risk of preeclampsia or eclampsia, but was not associated with risk of gestational hypertension.
Miller, 2022^18^; PCS, United States, Kapiolani Medical Center for Women and Children in Honolulu; Analytic N =55; - Age (y): 30.3±5.9; - Race/Ethnicity (%): NHW: 30.9; Native Hawaiian: 23.6; Filipino: 23.6; Japanese: 21.8; - Pre-pregnancy BMI (%): 25-29.9: 25.5; ≥30: 36.4; - Pre-existing DM (%): 0.0; - History of PE (%): 0.0 | HEI-2015, aMED, and DASH (continuous alignment); FFQ at: 11-13 GW, 18-20 GW, and 34-36 GW; DP Descriptions:; [underlined: HEI-2015]; - Positive components: Total vegetables; Greens and beans; Total fruit; Whole fruit; Fish; Whole grains; Total protein foods; Dairy; PUFA+MUFA:SFA; - Negative components: Refined grains; Calories from solid fat, added sugars, and alcohol; Sodium; [underlined: aMED]; - Positive components: Vegetables (excluding potatoes); Total fruit; Nuts; Legumes; Fish; Whole grains; MUFA: SFA; - Moderate component: Alcohol; - Negative component: Red and processed meat; [underlined: DASH]; - Positive components: Vegetables (excluding potatoes); Fruit; Nuts, seeds, and legumes; Fish; Low-fat dairy; - Negative components: Red and processed meat; SSB and fruit juice; Sodium; Outcome and assessment methods:; HDP assessed at: >20 GW; [underlined: HDP:] ≥140 mmHg SBP or ≥90 mmHg DBP on ≥2 occasions >4h apart; proteinuria; signs of end-organ damage, including serum Creatinine >1.1, AST/ALT 2x the upper boundary of the reference range, or platelets <100,000/dL | Hypertensive Disorders of Pregnancy; Logistic regression; OR (95% CI); [underlined: HEI-2015:] 0.89 (0.81, 0.99), p<0.05; [underlined: aMED:] 0.74 (0.40, 1.37), p≥0.05; [underlined: DASH:] 0.71 (0.55, 093), p<0.05 | Key confounders accounted for: Age, Race/ethnicity, Pre-pregnancy BMI, Parity, History of HDP, DM in current pregnancy; Other covariates: Excess GWG; Funding: Lakshmi Devi and Devraj Sharma Foundation; OLA Hawai’i Project; NIMHD; Summary: Greater alignment with the HEI-2015 and DASH was associated with reduced risk of hypertensive disorders of pregnancy. Alignment with the aMED was not associated with risk of hypertensive disorders of pregnancy.
Rifas-Shiman, 2099^19^; PCS, United States, Project Viva; Analytic N=1,777; - Age (y): 32.4±4.9; - Race/Ethnicity (%): White: 72; Other, ≥1 race: 16; Black/African American: 12; - SEP:; ○ Education (%): ≤High school: 9; College graduate: 69; ○ Household income <$40K (%): 13; - Pre-pregnancy BMI (%): 25-<30: 21; ≥30: 14; - Current GDM (%): ~5.0 | AHEI-P (continuous alignment9); FFQ at: 11.7±3.1 GW; DP Description:; - Positive components: vegetables, fruit, white meat (poultry or fish):red meat, fiber, PUFA:SFA, and folate, calcium, and iron from foods; - Negative component: trans fat; Outcome and assessment methods:; PE assessed at: >20 GW; [underlined: PE:] No chronic HTN but >140 mmHg SBP or >90 mmHg DBP w/ proteinuria (dipstick value of 1+ on ≥2 occasions or ≥2+ once) >4h but ≤7d apart; OR chronic HTN w/ proteinuria | Preeclampsia; Logistic regression; OR (95% CI) per 5 pt score increase; 0.96 (0.84, 1.10) | Key confounders accounted for: Age, Race/ethnicity, SEP, Parity, Pre-pregnancy BMI; Funding: NIH; Harvard Medical School; Harvard Pilgrim Health Care Foundation; Summary: Greater alignment with the AHEI-P was not associated with risk of preeclampsia.
Wiertsema, 2021^22^; PCS, The Netherlands, Generation R Study; Analytic N =Mid-pregnancy:; 3,299; Late-pregnancy: 3,321; - Age (y): 31.4±4.4; - Race/Ethnicity (%): Dutch: 100; - SEP:; ○ Higher education (%): 59.3; - Pre-pregnancy BMI: (%) ≥25: 22.2; - Preexistent HTN (%): 0.0; - Current GDM/DM (%): 0.0; - Smoking (%): 17.0 | DASH (quartiles of alignment); FFQ at: Median 13.5 GW; DP Description:; - Positive components: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy.; - Negative components: Red and Processed Meat; Sweetened Beverages; Sodium; Outcome and assessment methods:; BP assessed at: Mid pregnancy (median 20.4 GW) and late pregnancy (median 30.2 GW); Systolic and diastolic BP measured by investigators after 5 min rest | Systolic BP Regression model; β (95% CI), mm Hg; [underlined: Mid pregnancy]; Q1 vs. Q4 (Ref): 0.05 (−1.09, 1.18); Q2 vs. Q4 (Ref): 0.08 (−0.99, 1.15); Q3 vs. Q4 (Ref): −0.13 (−1.18, 0.91); Trend: −0.01 (−0.43, 0.40); [underlined: Late pregnancy]; Q1 vs. Q4 (Ref): −0.16 (−1.27, 0.96); Q2 vs. Q4 (Ref): 0.45 (−0.60, 1.49); Q3 vs. Q4 (Ref): −0.35 (−1.37, 0.68); Trend: 0.07 (−0.33, 0.48); Diastolic BP; Regression model; β (95% CI), mm Hg; [underlined: Mid pregnancy]; Q1 vs. Q4 (Ref): 1.31 (0.42, 2.21); Q2 vs. Q4 (Ref): 0.85 (0.01, 1.69); Q3 vs. Q4 (Ref): 0.33 (−0.49, 1.15); Trend: −0.45 (−0.78, −0.12); [underlined: Late pregnancy]; Q1 vs. Q4 (Ref): 0.09 (−0.79, 0.97); Q2 vs. Q4 (Ref): −0.01 (−0.84, 0.81); Q3 vs. Q4 (Ref): −0.21 (−1.02, 0.60); Trend: −0.06 (−0.38, 0.26) | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP,; Other covariates: Alcohol use, Folic acid use, TEI, Gestational age at time of measurement
Wiertsema, 2021^22^ cont.; Analytic N =3,414 | Outcome and assessment methods:; PE, Gestational HTN, HDP assessed at: >20 GW; Obtained from medical records.; [underlined: Gestational HTN:] Systolic BP ≥140 mm Hg and/or diastolic BP ≥90 mm Hg in previously normotensive participants; [underlined: PE:] Gestational HTN w/ proteinuria (≥2 dipsticks ≥2+, 1 catheter sample reading ≥1+, or ≥300mg in 24h urine); [underlined: Any HDP:] Gestational HTN or PE | Any HDP; Logistic regression; OR (95% CI); Q1 vs. Q4 (Ref): 1.14 (0.78, 1.67); Q2 vs. Q4 (Ref): 0.84 (0.56, 1.25); Q3 vs. Q4 (Ref): 0.95 (0.64, 1.40); Trend: 0.95 (0.83, 1.10); Gestational Hypertension; Logistic regression; OR (95% CI); Q1 vs. Q4 (Ref): 1.04 (0.67, 1.60); Q2 vs. Q4 (Ref): 0.91 (0.59, 1.42); Q3 vs. Q4 (Ref): 0.73 (0.46, 1.16); Trend: 0.96 (0.81, 1.12); Preeclampsia; Logistic regression; OR (95% CI); Q1 vs. Q4 (Ref): 1.46 (0.70, 3.07); Q2 vs. Q4 (Ref): 0.57 (0.23, 1.46); Q3 vs. Q4 (Ref): 1.74 (0.85, 3.55); Trend: 0.94 (0.72, 1.23) | Key confounders accounted for: Race/ethnicity, Pre-pregnancy BMI, Parity, History of HDP,; Other covariates: Folic acid use, gestational age at time of intake
Wiertsema, 2021^22^ cont.; Analytic N =Mid-pregnancy: 3,262; Late-pregnancy: 3,285 | Outcome and assessment methods:; BP assessed at: Mid pregnancy (median 20.4 GW) and late pregnancy (median 30.2 GW); Systolic and diastolic BP measured by investigators after 5 min rest | Excluding participants w/ pre-existent DM or GDM; Systolic BP Regression model; β (95% CI), mm Hg; [underlined: Mid pregnancy]; Q1 vs. Q4 (Ref): 0.01 (−1.14, 1.15); Q2 vs. Q4 (Ref): 0.06 (−1.02, 1.13); Q3 vs. Q4 (Ref): −0.18 (−1.22, 0.87); Trend: −0.01 (−0.43, 0.41); [underlined: Late pregnancy]; Q1 vs. Q4 (Ref): −0.26 (−1.38, 0.86); Q2 vs. Q4 (Ref): 0.38 (−0.67, 1.43); Q3 vs. Q4 (Ref): −0.34 (−1.37, 0.68); Trend: 0.10 (−0.31, 0.51); Diastolic BP; Regression model; β (95% CI), mm Hg; [underlined: Mid pregnancy]; Q1 vs. Q4 (Ref): 1.34 (0.44, 2.24), p<0.05; Q2 vs. Q4 (Ref): 0.82 (−0.02, 1.66); Q3 vs. Q4 (Ref): 0.30 (−0.52, 1.12); Trend: −0.47 (−0.80, −0.14), p<0.05; [underlined: Late pregnancy]; Q1 vs. Q4 (Ref): 0.04 (−0.84, 0.93); Q2 vs. Q4 (Ref): −0.08 (−0.91, 0.75); Q3 vs. Q4 (Ref): −0.26 (−1.07, 0.55); Trend: −0.04 (−0.36, 0.28) | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: Alcohol use, Folic acid use, TEI, Gestational age at time of measurement
Wiertsema, 2021^22^ cont.; Analytic N =3,378 | Outcome and assessment methods:; PE, Gestational HTN, HDP assessed at: >20 GW; Obtained from medical records.; [underlined: Gestational HTN]: Systolic BP ≥140 mm Hg and/or diastolic BP ≥90 mm Hg in previously normotensive participants; [underlined: PE:] Gestational HTN w/ proteinuria (≥2 dipsticks ≥2+, 1 catheter sample reading ≥1+, or ≥300mg in 24h urine); [underlined: Any HDP:] Gestational HTN or PE | Excluding participants w/ pre-existent DM or GDM; Any HDP; Logistic regression; OR (95% CI); Q1 vs. Q4 (Ref): 1.15 (0.79, 1.69); Q2 vs. Q4 (Ref): 0.79 (0.53, 1.20); Q3 vs. Q4 (Ref): 0.96 (0.65, 1.43); Trend: 0.96 (0.83, 1.11); Gestational Hypertension; Logistic regression; OR (95% CI); Q1 vs. Q4 (Ref): 1.04 (0.67, 1.61); Q2 vs. Q4 (Ref): 0.87 (0.55, 1.37); Q3 vs. Q4 (Ref): 0.74 (0.46, 1.18); Trend: 0.96 (0.82, 1.14); Preeclampsia; Logistic regression; OR (95% CI); Q1 vs. Q4 (Ref): 1.50 (0.72, 3.16); Q2 vs. Q4 (Ref): 0.50 (0.19, 1.33); Q3 vs. Q4 (Ref): 1.78 (0.87, 3.62); Trend: 0.93 (0.71, 1.22) | Key confounders accounted for: Race/ethnicity, Pre-pregnancy BMI, Parity, History of HDP, DM in current pregnancy; Other covariates: Folic acid use, Gestational age at time of intake; Funding: Erasmus Medical Center, Rotterdam; Erasmus University Rotterdam; the Netherlands Organization for Health Research and Development; the Netherlands Organisation for Scientific Research (NWO); the Ministry of Health, Welfare and Sport; the European Union’s Horizon 2020; the European Research Council; the Dutch Heart Foundation; the Dutch Diabetes Foundation; Summary: Lower alignment with DASH was associated with higher diastolic blood pressure during middle pregnancy in all participants and participants without pre-existing DM or GDM. No other comparisons were associated with diastolic blood pressure during middle or late pregnancy. Higher alignment with DASH was not associated with systolic blood pressure during middle or late pregnancy or risk of any hypertensive disorders of pregnancy, gestational hypertension, or preeclampsia.
Yee, 2020^23^; PCS, United States, nuMoM2b; Analytic N =8,259; - Age (y): Q1: 23.9±5.2; Q4: 29.9±4.5, p<0.001; - Race/Ethnicity (%): NHW: Q1: 47.8; Q4: 74.4; NHB: Q1: 24.0; Q4: 2.8; Hispanic: Q1: 20.3; Q4: 11.9; Other: Q1: 6.3; Q4: 4.0; Asian: Q1: 1.5; Q4: 6.9, p<0.001; - SEP:; ○ Public insurance (%): Q1: 50.7; Q4: 8.4, p<0.001; ○ Household income <200% FPL (%): Q1: 55.7; Q4: 12.4, p<0.001; ○ ≥Some college (%): Q1: 82.0; Q4: 98.8, p<0.001; - Pre-pregnancy BMI: Q1: 27.1±7.3; Q4: 24.9±4.9, p<0.001; - History of HDP (%): 100% nulliparous; - Pregestational DM (%): Q1: 2.0; Q2: 1.7; Q3: 1.5; Q4: 0.8, p=0.018; - Current GDM (%): 4.2; - Smoking (%): Ever used tobacco: Q1: 50.7; Q4: 36.6, p<0.001 | HEI-2010 (quartiles of alignment); FFQ at: 6-13 GW; DP Description:; - Positive components: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids; - Negative components: Refined Grains; Empty Calories (i.e., energy from solid fats, alcohol, and added sugars); Sodium; Outcome and assessment methods:; HDP assessed at: >20 GW; [underlined: HDP]: Antepartum gestational HTN, or antepartum, intrapartum, or postpartum (≤14d) PE, eclampsia, or superimposed PE; [underlined: Gestational HTN]: New onset SBP ≥140mmHg or DBP ≥90mmHg twice ≥4h apart; [underlined: PE]: Gestational HTN w proteinuria (≥0.3g protein in 24h urine); [underlined: Eclampsia:] New-onset tonic-clonic, focal, or multifocal seizures in the absence of other causative conditions | Hypertensive Disorders of Pregnancy; Multivariable Poisson Regression; RR (95% CI); Q1 vs. Q4 (Ref): 1.13 (1.00, 1.29), p≥0.05; Q2 vs. Q4 (Ref): 1.10 (0.98, 1.24), p≥0.05; Q3 vs. Q4 (Ref): 1.05 (0.93, 1.19), p≥0.05 | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: Chronic HTN, Mental health disorder, Marital status; Funding: NICHD; Clinical and Translational Science Institutes of Indiana University and UC Irvine; Summary: Alignment with the HEI-2010 was not associated with risk of hypertensive disorders or pregnancy.
Factor/Cluster Analysis
Brantsæter, 2009^2^; PCS, Norway, MoBa; Analytic N=23,423; - Age (%): <20: 3.8; 30-39: 37.2; ≥40: 0.9; - Race/Ethnicity (%): White: >99; - SEP:; ○ Education (%): ≤10y: 4.0; 11-12y: 31.4; ≥16y: 20.5; - Pre-pregnancy BMI (%): 25-29: 19.9; ≥30: 8.5; - History of HTN (%): 0.9; - Smoking (%): Occasional: 3.2; Daily: 5.4 | Vegetable DP, Processed food DP, Potato and fish DP, & Cakes and sweets DP (tertiles of alignment); FFQ at: 20.7±3.7 GW; DP Descriptions:; - Vegetable DP: Higher in vegetables, cooking oil, olive oil, fruits and berries, rice, and chicken; - Processed food DP: Higher in processed meat products, white bread, French fries, salty snacks, and sugar-sweetened drinks and high negative loadings on oily fish, high-fiber breakfast cereals, and lean fish; - Potato and fish DP: Higher in cooked potatoes, processed fish, lean fish, fish spread and shellfish, and margarine; - Cakes and sweets DP: Higher in cakes, waffles and pancakes, buns, ice cream, sweet biscuits, sweets, and chocolate; Outcome and assessment methods:; PE assessed at: >20 GW; [underlined: PE:] Reported preeclampsia (>140 mmHg/90 mmHg BP w/ proteinuria >1+ dipstick on ≥2 occasions), HELLP syndrome (hemolysis, elevated liver enzymes, and low platelet count), eclampsia, early preeclampsia (<34 GW), mild preeclampsia, and severe preeclampsia on the birth notification form | Preeclampsia; Multiple Logistic Regression; OR (95% CI); [underlined: Vegetable DP]; T2 vs. T1 (Ref): 0.84 (0.73, 0.97); T3 vs. T1 (Ref): 0.72 (0.62, 0.85); [underlined: Processed food DP]; T2 vs. T1 (Ref): 1.06 (0.91, 1.23); T3 vs. T1 (Ref): 1.21 (1.03, 1.41); [underlined: Potato and fish DP]; T2 vs. T1 (Ref): 0.99 (0.86, 1.15); T3 vs. T1 (Ref): 1.00 (0.84, 1.18); [underlined: Cakes and sweets DP]; T2 vs. T1 (Ref): 1.00 (0.86, 1.15); T3 vs. T1 (Ref): 0.90 (0.76, 1.06) | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, History of HDP; Other covariates: Other DP, Height, TEI, Supplement use; Funding: Norwegian Ministry of Health; Norwegian Ministry of Education and Research; NIH/NIEHS; NIH/NINDS; Norwegian Research Council/FUGE; European Commission, 6th Framework Programme, Priority 5 on Food Quality and Safety; Summary: Greater alignment with the Vegetable DP was associated with reduced risk of preeclampsia. Greater alignment with the Processed DP was associated with greater risk of preeclampsia. Greater alignment with the Potato and fish DP and the Cakes and sweets DP was not associated with risk of preeclampsia.
de Seymour, 2022^4^; PCS, China, CLIMB; Analytic N =962; - Age (y): Median (IQR): 28 (26, 31); - Race/Ethnicity (%): Han ethnicity: 97.9; - SEP:; ○ Tertiary level education (%): 63.1; ○ Household income (%): <7,000 yuan/mo: 19.5; >10,000 yuan/mo: 44.5; - Baseline BMI: Median (IQR): 21.0 (19.4, 22.9); - Current GDM (%): 27.7; - Previous pregnancy complication resulting in delivery <32 GW (%): 0.0 | FPV DP & PSO DP (continuous alignment); FFQ at: 11-14 GW; DP Description:; - Fish, poultry and vegetables (FPV)-based DP: Higher in fish; poultry; legumes and bean products; green leafy vegetables; root vegetables; other vegetables; seafood; fruits; eggs; organ meats; beverages; bread; dairy; soup; nuts; - Pasta, sweetened beverages, oils and condiments (PSO)-based DP: Higher in pasta; sweetened beverages; oils and condiments; fast food; Outcome and assessment methods: PE assessed at: >20 GW; [underlined: PE:] Systolic BP >140 mmHg and/or diastolic BP >90 mmHg on at least two occasions 4 hr apart w/ significant proteinuria (spot urine protein/creatinine >30 mg/mmol or >300 mg/d or ≥1g/L [“2 +”] on dipstick testing) | Preeclampsia; Binomial logistic regression; OR (95% CI); [underlined: FPV-based DP:] 1.106 (0.665, 1.838), p=0.689; [underlined: PSO-based DP:] 0.909 (0.499, 1.654), p=0.755 | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, History of HDP; Other covariates: Offspring sex, TEI, CLIMB treatment group, Other DP; Funding: Joint Health Research Council New Zealand–National Science Foundation of China; Lottery Health New Zealand; Fonterra Co-operative Group Ltd., New Zealand; New Zealand Ministry for Primary Industries; Summary: Alignment with the FPV-based DP and PSO-based DP was not associated with risk of preeclampsia.
Flynn, 2016^8^; PCS, United Kingdom, UPBEAT; Analytic N =984; - Age (y): 30.5±5.5; - Race/Ethnicity (%): White: 64; Black: 23; Asian: 8; Other: 5; - SEP:; ○ Education (%): None/Secondary: 20; Degree/Higher degree: 40; Vocational qualification: 24; ○ Index of multiple deprivation (%): 1 (least deprived): 4; 5 (most deprived): 43; - Pre-pregnancy BMI: 36.2±4.7; ○ (%): ≥30: 100; - Pre-pregnancy HTN: 0.0; - Pre-pregnancy DM: 0.0 | Fruit & Veg DP & Snacks DP (quartiles of alignment) FFQ at: 15-<19 GW; DP Description:; - Fruit & Veg DP: High intake of bananas; citrus fruit; dried fruit; fresh fruit; green vegetables; pulses; root vegetables; salad vegetables; tropical fruit; yoghurt; - Snacks DP: High intake of biscuits and cookies; cakes and pastries; chocolate; full fat cheese; sweets; Outcome and assessment methods:; PE assessed at: NR; [underlined: PE:] Systolic BP ≥140 mm Hg or diastolic BP ≥90 mm Hg on ≥2 occasions ≥4h apart, w/ proteinuria ≥300 mg/24h or spot urine protein:creatinine ratio ≥30 mg/mmol creatinine, or urine dipstick protein ≥2+ | Preeclampsia; Multiple logistic regression; OR (95% CI); [underlined: Fruit & Veg DP]; Q2 vs. Q1 (Ref): 0.88 (0.36, 2.13); Q3 vs. Q1 (Ref): 0.58 (0.22, 1.54); Q4 vs. Q1 (Ref): 0.61 (0.23, 1.66); p for trend=0.641; [underlined: Snacks DP]; Q2 vs. Q1 (Ref): 1.14 (0.40, 3.23); Q3 vs. Q1 (Ref): 1.41 (0.51, 3.94); Q4 vs. Q1 (Ref): 1.22 (0.43, 3.46); p for trend=0.924 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Parity, DM in current pregnancy; Other covariates: Treatment allocation
Flynn, 2016^8^ cont. | African/Caribbean DP & Processed DP (quartiles of alignment); FFQ at: 15-<19 GW; DP Description:; - African/Caribbean DP: High intake of red meat; cassava; white meat; rice including pilau, fried or jollof rice; plantain; fish; - Processed DP: High intake of chocolate; crisps; green vegetables; potatoes; processed meat and meat products; root vegetables; squash and fizzy drinks; sugar free squash and fizzy drinks; chips | Preeclampsia; Multiple logistic regression; OR (95% CI); [underlined: African/Caribbean DP]; Q2 vs. Q1 (Ref): 0.79 (0.35, 1.80); Q3 vs. Q1 (Ref): 0.42 (0.15, 1.14); Q4 vs. Q1 (Ref): 0.42 (0.12, 1.45); p for trend=0.298; [underlined: Processed DP]; Q2 vs. Q1 (Ref): 0.86 (0.32, 2.33); Q3 vs. Q1 (Ref): 0.51 (0.16, 1.62); Q4 vs. Q1 (Ref): 1.40 (0.55, 3.54); p for trend=0.291 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Parity,; Other covariates: Treatment allocation; Funding: NIHR UK; Scottish Government Health Directorates; Guys and St. Thomas’ Charity; Tommy’s Charity; the European Union’s Seventh Framework Programme; Summary: Among participants with pre-pregnancy BMI ≥30, alignment with the Fruit & Veg DP, African/Caribbean DP, Processed DP, and Snacks DP was not associated with risk of preeclampsia.
Hajianfar, 2018^9^; PCS, Iran (Islamic Rep. of), Isfahan University of Medical Sciences; Analytic N=812; - Age (y): 20-40; - SEP:; ○ Occupation (%): Healthy: Homemaker: Q1: 25.3; Q4: 22.2; Employed: Q1: 21.4; Q4: 38.1; Teacher: Q1: 28.9; Q4: 28.9, p=0.01; Western: p=0.4; Traditional: p=0.3; ○ Education (%): Traditional: Undergraduate: Q1: 21.3; Q4: 23; Graduate: Q1: 28.2; Q4: 26.4, p=0.03; Healthy: p=0.9; Western: p=0.4; ○ SES (%): Western: Low: Q1: 32.8; Q4: 14.1; High: Q1: 24.3; Q4: 28.5, p=0.02; Traditional: Low: Q1: 12.5; Q4: 20.3; High: Q1: 27.2; Q4: 30.3, p<0.001; Healthy: p=0.5; - Pre-pregnancy BMI (%): ≥25: Healthy: Q1: 24.2; Q4: 26.1; Western: Q1: 24.7; Q4: 23.6; Traditional: Q1: 26.1; Q4: 25.6 | Healthy DP, Western DP, & Traditional DP (quartiles of alignment); FFQ at: 8-16 GW; DP Description:; - Healthy DP: Higher intake of green vegetables, leafy vegetables, colored vegetables, fruits, low fat dairy, poultry, bulky vegetables, red meat, citrus, nuts, fish, olive, marinades, sweet fruit, egg, and unsaturated fat; - Western DP: Higher intake of processed meats, fruits, fruits juice, citrus, nuts, fish, desserts and sweets, sugar, saturated fat, sweet fruit (melon, persimmon, date, fig, grapes, raisins, berries that have high glycemic index), potato, legumes, coffee, egg, pizza, high fat dairy, whole grain, and soft drinks; - Traditional DP: Higher intake of refined grains, colored vegetables, olive, sugar, salt, spices, unsaturated fat, garlic, onion, and tea; Outcome and assessment methods:; PE and Gestational HTN assessed at: ≥20 GW; [underlined: Gestational HTN:] SBP ≥140 mmHg or DBP ≥90 mmHg on ≥2 occasions ≥4-6h apart; [underlined: PE:] Gestational HTN with proteinuria (≥300 mg/L in 24h urine sample) | Preeclampsia; Logistic regression, p-values from Mantel– Haenszel extension chi-squared test; OR (95% CI); [underlined: Healthy DP]; Q2 vs. Q1 (Ref): 0.92 (0.46, 1.82), p.0.05; Q3 vs. Q1 (Ref): 0.44 (0.21, 0.92), p<0.05; Q4 vs. Q1 (Ref): 0.49 (0.24, 1), p≥0.05; p=0.05; [underlined: Western DP]; Q2 vs. Q1 (Ref): 3.25 (1.51, 6.99), p<0.05; Q3 vs. Q1 (Ref): 2.02 (0.97. 4.20), p≥0.05; Q4 vs. Q1 (Ref): 2.08 (1, 4.36), p≥0.05; p=0.02; [underlined: Traditional DP]; Q2 vs. Q1 (Ref): 1.27 (0.64, 2.55), p≥0.05; Q3 vs. Q1 (Ref): 1.41 (0.68, 2.93), p≥0.05; Q4 vs. Q1 (Ref): 1.25 (0.63, 2.49), p≥0.05; p=0.8; High Diastolic BP; Logistic regression, p-values from Mantel–Haenszel extension chi-squared test; OR (95% CI); [underlined: Healthy DP]; Q2 vs. Q1 (Ref): 0.49 (0.13, 1.78), p≥0.05; Q3 vs. Q1 (Ref): 0.68 (0.2, 2.2), p≥0.05; Q4 vs. Q1 (Ref): 0.22 (0.04, 1.14), p≥0.05; p=0.31; [underlined: Western DP]; Q2 vs. Q1 (Ref): 1.03 (0.33, 3.2), p≥0.05; Q3 vs. Q1 (Ref): 0.44 (0.11, 1.63), p≥0.05; Q4 vs. Q1 (Ref): 0.1 (0. 01, 0.95), p<0.05; p=0.13; [underlined: Traditional DP]; Q2 vs. Q1 (Ref): 1.44 (0.41, 5.09), p≥0.05; Q3 vs. Q1 (Ref): 0.57 (0.13, 2.38), p≥0.05; Q4 vs. Q1 (Ref): 0.86 (0.21, 3.45), p≥0.05 p=0.58; High Systolic BP; Logistic regression, p-values from Mantel–Haenszel extension chi-squared test; OR (95% CI); [underlined: Healthy DP]; Q2 vs. Q1 (Ref): 0.83 (0.37, 1.86), p≥0.05; Q3 vs. Q1 (Ref): 0.81 (0.36, 1.80), p≥0.05; Q4 vs. Q1 (Ref): 0.58 (0.24, 1.40), p≥0.05; p=0.7; [underlined: Western DP]; Q2 vs. Q1 (Ref): 0.63 (0.3, 1.3), p≥0.05; Q3 vs. Q1 (Ref): 0.36 (0.15, 0.81), p<0.05; Q4 vs. Q1 (Ref): 0.13 (0.04, 0.42), p<0.05; p=0.002; [underlined: Traditional DP]; Q2 vs. Q1 (Ref): 1.03 (0.44, 2.36), p≥0.05; Q3 vs. Q1 (Ref): 0.74 (0.31, 1.76), p≥0.05; Q4 vs. Q1 (Ref): 1.07 (0.47, 2.44), p≥0.05; p=0.83 | Key confounders accounted for: Age, Physical activity, SEP, Pre-pregnancy BMI, DM in current pregnancy; Other covariates: TEI; Funding: NR; Summary: Greater alignment with the Healthy DP was marginally associated with reduced risk of preeclampsia. Greater alignment with the Western DP was associated with higher risk of preeclampsia. Alignment with the Traditional DP was not associated with risk of preeclampsia.; High alignment with the Western DP was associated with reduced risk of high diastolic blood pressure when compared to low alignment, but the overall association across quartiles was not significant. Alignment with the Healthy DP or Traditional DP was not associated with risk of high diastolic blood pressure.; Greater alignment with the Western DP was associated with reduced risk of high systolic blood pressure. Alignment with the Healthy DP or Traditional DP was not associated with risk of high systolic blood pressure.
Hu, 2022^12^; PCS, China, BISCS; Analytic N =1,092; - Age (%): <25: 5.9; >35: 15.6; - Race/Ethnicity (%): Chinese Han: 83.4; Other: 16.6; - SEP:; ○ Education (%): ≤High school: 24.0; ○ Household income (%): <50K CNY/y: 53.6; - Pre-pregnancy BMI (%): ≥24.0: 26.5; - History of HTN (%): 0.3; - History of DM (%): 0.2; - Current GDM (%): 22.3; - Smoking (%): 0.6 | Traditional DP-TFD, Wheaten food-coarse cereals DP-TFD, Sweet food–seafood DP-TFD, Fried food–protein-rich DP-TFD, Fish-seafood DP-FFQ, Protein-rich DP-FFQ, & Vegetable–fruit–rice DP-FFQ (quartiles of alignment); 3d food diaries (TFD) at: 22±1.2 to 24±1.2 GW; FFQ at: 22±1.2 w; DP Descriptions:; - Traditional DP-TFD: Higher in tubers; vegetables; fruits; red meat; coarse cereals; rice; nuts; - Wheaten food-coarse cereals DP-TFD: Higher intakes of wheat flour and products; coarse cereals; beans and bean products; lower intakes of eggs; rice; - Sweet food–seafood DP-TFD: Higher intakes of pastries and candies; sweet beverages; shrimps, crabs, and mussels; fruits; - Fried food–protein-rich DP-TFD: Higher intakes of fried foods; beans and bean products; dairy products; - Fish-seafood DP-FFQ: Higher intakes of shrimps, crabs and mussels; marine fish; freshwater fish; organ meat; seaweed; poultry; - Protein-rich DP-FFQ: Higher intakes of dairy products; milk; eggs; beans and bean products; nuts; pastries and candies; - Vegetable–fruit–rice DP-FFQ: Higher intakes of vegetables; fruits; rice; nuts; Outcome and assessment methods:; BP assessed at: Each antenatal visit (median 7 times); BP measured after 5 min rest. Systolic BP and Diastolic BP calculated as average of 3 measurements.; MAP calculated as 1/3 SBP + 2/3 DBP. | Diastolic BP; Linear regression; β (95% CI); [underlined: Traditional DP-TFD]; Q2 vs Q1 (Ref): 0.05 (−1.01, 1.11); Q3 vs Q1 (Ref): 0.21 (−0.94, 1.35); Q4 vs Q1 (Ref): 0.71 (−0.61, 2.02); p for trend=0.249; [underlined: Wheaten food-coarse cereals DP-TFD]; Q2 vs Q1 (Ref): 0.37 (−0.65, 1.40); Q3 vs Q1 (Ref): 0.28 (−0.78, 1.34); Q4 vs Q1 (Ref): −0.12 (−1.18, 0.93); p for trend=0.847; [underlined: Sweet food-seafood DP-TFD]; Q2 vs Q1 (Ref): −0.09 (−1.13, 0.95); Q3 vs Q1 (Ref): 0.04 (−1.01, 1.09); Q4 vs Q1 (Ref): −1.04 (−2.10, 0.02); p for trend=0.031; [underlined: Fried food-protein-rich DP-TFD]; Q2 vs Q1 (Ref): 0.12 (−0.92, 1.16); Q3 vs Q1 (Ref): −0.12 (−1.18, 0.94); Q4 vs Q1 (Ref): 0.22 (−0.87, 1.31); p for trend=0.665; [underlined: Fish-seafood DP-FFQ]; Q2 vs Q1 (Ref): −1.23 (−2.33, 0.14); Q3 vs Q1 (Ref): 0.07 (−1.07, 1.22); Q4 vs Q1 (Ref): 0.52 (−0.72, 1.77); p for trend=0.057; [underlined: Protein-rich DP-FFQ]; Q2 vs Q1 (Ref): 0.55 (−0.54, 1.64); Q3 vs Q1 (Ref): 0.63 (−0.54, 1.81); Q4 vs Q1 (Ref): 0.17 (−1.14, 1.48); p for trend=0.869; [underlined: Vegetable-fruit-rice DP-FFQ]; Q2 vs Q1 (Ref): 0.05 (−1.00, 1.11); Q3 vs Q1 (Ref): −0.45 (−1.52, 0.62); Q4 vs Q1 (Ref): −0.48 (−1.60, 0.63); p for trend=0.331; Systolic BP Linear regression; β (95% CI); [underlined: Traditional DP-TFD]; Q2 vs Q1 (Ref): −0.25 (−1.87, 1.36); Q3 vs Q1 (Ref): 0.34 (−1.41, 2.08); Q4 vs Q1 (Ref): 0.93 (−1.06, 2.93); p for trend=0.218; [underlined: Wheaten food-coarse cereals DP-TFD]; Q2 vs Q1 (Ref): −0.74 (−2.30, 0.82); Q3 vs Q1 (Ref): −1.21 (−2.82, 0.41); Q4 vs Q1 (Ref): −1.44 (−3.05, 0.17); p for trend=0.061; [underlined: Sweet food-seafood DP-TFD]; Q2 vs Q1 (Ref): −1.53 (−3.11, 0.05); Q3 vs Q1 (Ref): −0.17 (−1.77, 1.43); Q4 vs Q1 (Ref): −2.57 (−4.19, −0.96); p for trend=0.005; [underlined: Fried food-protein-rich DP-TFD]; Q2 vs Q1 (Ref): −0.73 (−2.32, 0.85); Q3 vs Q1 (Ref): 0.05 (−1.67, 1.57); Q4 vs Q1 (Ref): 0.81 (−0.85, 2.47); p for trend=0.141; [underlined: Fish-seafood DP-FFQ]; Q2 vs Q1 (Ref): −2.17 (−3.84, −0.50); Q3 vs Q1 (Ref): 0.39 (−1.35, 2.14); Q4 vs Q1 (Ref): −0.60 (−2.49, 1.30); p for trend=0.693; [underlined: Protein-rich DP-FFQ]; Q2 vs Q1 (Ref): −0.18 (−1.84, 1.48); Q3 vs Q1 (Ref): 1.47 (−0.33, 3.26); Q4 vs Q1 (Ref): 1.03 (−0.97, 3.03); p for trend=0.214; [underlined: Vegetable-fruit-rice DP-FFQ]; Q2 vs Q1 (Ref): 0.75 (−0.85, 2.36); Q3 vs Q1 (Ref): −0.78 (−2.42, 0.86); Q4 vs Q1 (Ref): −0.41 (−2.11, 1.29); p for trend=0.345; Mean Arterial Pressure; Linear regression; β (95% CI); [underlined: Traditional DP-TFD]; Q2 vs Q1 (Ref): −0.11 (−1.28, 1.05); Q3 vs Q1 (Ref): 0.21 (−1.04, 1.47); Q4 vs Q1 (Ref): 0.71 (−0.72, 2.15); p for trend=0.232; [underlined: Wheaten food-coarse cereals DP-TFD]; Q2 vs Q1 (Ref): 0.03 (−1.09, 1.15); Q3 vs Q1 (Ref): −0.25 (−1.41, 0.91); Q4 vs Q1 (Ref): −0.57 (−1.73, 0.59); p for trend=0.306; [underlined: Sweet food-seafood DP-TFD]; Q2 vs Q1 (Ref): −0.57 (−1.70, 0.57); Q3 vs Q1 (Ref): −0.05 (−1.20, 1.10); Q4 vs Q1 (Ref): −1.54 (−2.70, −0.38); p for trend=0.009; [underlined: Fried food-protein-rich DP-TFD]; Q2 vs Q1 (Ref): −0.13 (−1.26, 1.01); Q3 vs Q1 (Ref): 0.01 (−1.15, 1.18); Q4 vs Q1 (Ref): 0.51 (−0.68, 1.71); p for trend=0.265; [underlined: Fish-seafood DP-FFQ]; Q2 vs Q1 (Ref): −1.44 (−2.64, −0.24); Q3 vs Q1 (Ref): 0.18 (−1.07, 1.43); Q4 vs Q1 (Ref): 0.20 (−1.16, 1.56); p for trend=0.176; [underlined: Protein-rich DP-FFQ]; Q2 vs Q1 (Ref): 0.32 (−0.88, 1.51); Q3 vs Q1 (Ref): 0.97 (−0.32, 2.26); Q4 vs Q1 (Ref): 0.56 (−0.88, 1.99); p for trend=0.522; [underlined: Vegetable-fruit-rice DP-FFQ]; Q2 vs Q1 (Ref): 0.12 (−1.03, 1.28); Q3 vs Q1 (Ref): −0.65 (−1.82, 0.53); Q4 vs Q1 (Ref): −0.55 (−1.77, 0.67); p for trend= 0.259; Further adjustment for GWG or GDM did not substantively change the results | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP, DM in current pregnancy; Other covariates: TEI; Other DP from same assessment tool (TFD or FFQ);; Funding: None; Summary: Greater alignment with the Sweet food-seafood-TFD DP was associated with lower diastolic BP (DBP), systolic BP (SBP), and mean arterial pressure (MAP). Greater alignment with the Wheaten food-coarse cereal-TFD DP neared significance for an association with lower SBP, and the direction of effect was suggestive for DBP and MAP, despite statistical non-significance. Greater alignment with the Fish-seafood-FFQ DP neared significance for an association with higher DBP, and the direction of effect was suggestive for MAP, but not SBP. There were no associations between the Vegetable-fruit-rice-FFQ DP, the Traditional-TFD DP, Protein-rich-FFQ DP, or Fried food-protein-rich-TFD DP and all BP measures.
Hu, 2022^12^ cont. | Outcome and assessment methods:; Gestational HTN assessed at: >20 GW; Gestational HTN: Systolic BP >140 mmHg or Diastolic BP >90mmHg (≥2 times, ≥4h apart) | Gestational Hypertension; Logistic regression; OR (95% CI); [underlined: Traditional DP-TFD]; Q2 vs Q1 (Ref): 0.79 (0.48, 1.29); Q3 vs Q1 (Ref): 0.60 (0.35, 1.03); Q4 vs Q1 (Ref): 0.74 (0.42, 1.31); p for trend=0.347; DP*pre-pregnancy BMI p for interaction ≥0.05; [underlined: Wheaten food-coarse cereals DP-TFD]; Q2 vs Q1 (Ref): 0.68 (0.41, 1.10); Q3 vs Q1 (Ref): 0.53 (0.31, 0.90); Q4 vs Q1 (Ref): 0.71 (0.43, 1.16); p for trend=0.122; DP*pre-pregnancy BMI p for interaction ≥0.05; [underlined: Sweet food-seafood DP-TFD]; All participants; Q2 vs Q1 (Ref): 0.79 (0.48, 1.33); Q3 vs Q1 (Ref): 0.93 (0.57, 1.54); Q4 vs Q1 (Ref): 0.80 (0.48, 1.35); p for trend=0.474; Pre-pregnancy BMI ≥24; Q2 vs. Q1 (Ref): 0.49, p≥0.05; Q3 vs. Q1 (Ref): 0.69, p≥0.05; Q4 vs. Q1 (Ref): 0.30 (0.16, 1.00); Pre-pregnancy BMI <24; Q2 vs. Q1 (Ref): 1.08, p≥0.05; Q3 vs. Q1 (Ref): 1.22, p≥0.05; Q4 vs. Q1 (Ref): 1.36 (0.70, 2.66); DP*pre-pregnancy BMI p for; interaction=0.045; [underlined: Fried food-protein-rich DP-TFD]; Q2 vs Q1 (Ref): 0.86 (0.51, 1.46); Q3 vs Q1 (Ref): 0.98 (0.58, 1.65); Q4 vs Q1 (Ref): 1.51 (0.91, 2.51); p for trend=0.052; DP*pre-pregnancy BMI p for interaction; ≥0.05; [underlined: Fish-seafood DP-FFQ]; All participants; Q2 vs Q1 (Ref): 0.74 (0.42, 1.29); Q3 vs Q1 (Ref): 1.07 (0.62, 1.85); Q4 vs Q1 (Ref): 1.04 (0.57, 1.88); p for trend=0.567; Pre-pregnancy BMI ≥24; Q2 vs. Q1 (Ref): 0.28, p<0.05; Q3 vs. Q1 (Ref): 0.40 (0.16, 0.99); Q4 vs. Q1 (Ref): 0.41, p≥0.05; Pre-pregnancy BMI <24; Q2 vs. Q1 (Ref): 1.57, p≥0.05; Q3 vs. Q1 (Ref): 2.12 (0.98, 4.59); Q4 vs. Q1 (Ref): 2.20, p≥0.05; DP*pre-pregnancy BMI p for interaction=0.007; [underlined: Protein-rich DP-FFQ]; Q2 vs Q1 (Ref): 0.89 (0.52, 1.55); Q3 vs Q1 (Ref): 1.35 (0.76, 2.39); Q4 vs Q1 (Ref): 1.14 (0.60, 2.17); p for trend=0.552; DP*pre-pregnancy BMI p for interaction ≥0.05; [underlined: Vegetable-fruit-rice DP-FFQ]; Q2 vs Q1 (Ref): 0.89 (0.53, 1.48); Q3 vs Q1 (Ref): 0.93 (0.55, 1.57); Q4 vs Q1 (Ref): 0.84 (0.48, 1.46); p for trend=0.643; DP*pre-pregnancy BMI p for interaction ≥0.05; Further adjustment for GWG or GDM did not change the results in general | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity,; Other covariates: Other DPs from same assessment tool (TFD or FFQ), total energy intake per day, and history of diabetes; Funding: None; Summary: Greater alignment with the Fried food-protein-rich-TFD DP neared significance for an association with higher risk of gestational hypertension. There was a statistically significant interaction between the Sweet foodseafood-TFD DP and Fish-seafoodFFQ DP and pre-pregnancy BMI: greater alignment to these DP was associated with lower risk of gestational hypertension among those with BMI ≥24, but not among those with BMI <24. Alignment with the Traditional-TFD DP, Wheaten food-coarse cereals-TFD DP, Protein-rich-FFQ DP, and Vegetable-fruit-rice-FFQ DP was not associated with risk of gestational hypertension.
Ikem, 2019^13^; PCS, Denmark, DNBC; Analytic N =55,139; - Age (y):; ○ GHTN: 30±4.3; No GHTN: 30.4±4.2, p<0.0001; ○ PE: 29.8±4.5; No PE: 30.3±4.3, p<0.0001; ○ Severe PE: 30.0±4.4; No Severe PE: 30.3±4.3, p=0.06; - Sociodemographic status of pair (%):; ○ GHTN: High: 18.3; Low: 41.8; No GHTN: High: 22.8; Low: 37.7, p<0.0001; ○ PE: High: 18.1; Low: 41.4; No PE: High: 22.6; Low: 37.7, p<0.001; - Pre-pregnancy BMI:; ○ GHTN: 25.4±5.1; No GHTN: 23.3±4.0, p<0.0001; ○ PE: 25.8±5.4; No PE: 23.5±4.1, p<0.0001; ○ Severe PE: 25.1±5.0; No Severe PE: 23.5±4.2, p<0.0001; - History of HTN (%):; ○ GHTN: 13.3; No GHTN: 2.6, p<0.0001; ○ PE: 11.4; No PE: 3.7, p<0.0001; ○ Severe PE: 10.7; No Severe PE: 3.9, p<0.0001; - Current GDM (%): ~1.0; - Smoking (%):; ○ GHTN: 25.8; No GHTN: 24.7, p=0.02; ○ PE: 20.2; No PE: 25.1, p=0.00; ○ Severe PE: 16.7; No Severe PE: 25.0, p=0.02 | Western DP, Vegetable/Prudent DP, Seafood DP, Nordic DP, Rice/Pasta/Poultry DP, Sweets DP, & Alcohol DP (quintiles of alignment); FFQ at: 25 GW; DP Descriptions:; - Western DP: Higher in pork; beef and veal; mixed meat; cold meat; egg; potatoes; French fries; dressing sauce; white bread; cold fish; butter; margarine; - Vegetable/Prudent DP: Higher in legumes; root vegetables; tomato; salad; corn; mushroom; onion; cabbage; other vegetables; other fruit; - Seafood DP: Higher in lean fish; oily fish; shellfish; cold fish; smoked fish; oil; beef and veal; lamb; egg; onion; tomato; Asian vegetables; other vegetables; fermented milk; yogurt; - Nordic DP: Higher in dark bread; Nordic fruit; hard cheese; banana; dried fruit; sweet spread; cold meat; - Rice/Pasta/Poultry DP: Higher in rice; pasta; poultry; - Sweets DP: Higher in chocolate; dairy dessert; candy; sweet spread; sugar cakes; white bread; margarine; snacks; French fries; - Alcohol DP: Higher in liquor; wine; beer; soybean; root vegetables; berries; Outcome and assessment methods:; Total Gestational HTN and PE assessed at: >20 GW; Mid Gestational HTN assessed at: 20-30 GW; Late Gestational HTN assessed at: >30 GW; Gestational HTN self-reported. Total and severe PE defined based on doctor diagnosis; [underlined: Gestational HTN:] New-onset HTN (≥140/90 mmHg) w/o proteinuria; [underlined: Total PE:] Elevated BP (≥140/90 mmHg) w/ proteinuria (≥300 mg/24h or 1+ urine dipstick); [underlined: Severe PE:] Severe elevated BP (≥160/110 mmHg), proteinuria (≥500 mg/24h or 3+ urine dipstick), or complications/clinical manifestations of severity including cerebral or visual disturbance, oliguria, HELLP syndrome, or eclampsia | Gestational Hypertension (Analytic N=39,362); Multivariable logistic regression OR (95% CI); [underlined: Western DP]; All participants; Q5 vs. Q1 (Ref): 1.18 (1.05, 1.33); Q4 vs. Q1 (Ref): 1.08 (0.97, 1.20); Q3 vs. Q1 (Ref): 1.16 (1.05, 1.29); Q2 vs. Q1 (Ref): 1.13 (1.03, 1.25); p for trend=0.03; Pre-pregnancy BMI <18.5; Q5 vs. Q1 (Ref): 1.18 (0.56, 2.47); Q4 vs. Q1 (Ref): 0.78 (0.38, 1.60); Q3 vs. Q1 (Ref): 0.84 (0.41, 1.73); Q2 vs. Q1 (Ref): 1.15 (0.60, 2.23); p for trend=0.81; Pre-pregnancy BMI 18.5-24.9; Q5 vs. Q1 (Ref): 1.23 (1.05, 1.44); Q4 vs. Q1 (Ref): 1.07 (0.92, 1.23); Q3 vs. Q1 (Ref): 1.12 (0.98, 1.28); Q2 vs. Q1 (Ref): 1.09 (0.96, 1.24); p for trend=0.03; Pre-pregnancy BMI ≥25; Q5 vs. Q1 (Ref): 0.97 (0.80, 1.18); Q4 vs. Q1 (Ref): 0.99 (0.83, 1.18); Q3 vs. Q1 (Ref): 1.12 (0.94, 1.33); Q2 vs. Q1 (Ref): 1.07 (0.91, 1.27); p for trend=0.39; Male Fetal Sex; Q5 vs. Q1 (Ref): 1.10 (0.93, 1.29); Q4 vs. Q1 (Ref): 1.15 (1.00, 1.33); Q3 vs. Q1 (Ref): 1.06 (0.92, 1.22); Q2 vs. Q1 (Ref): 1.13 (0.98, 1.29); p for trend=0.30; Female Fetal Sex; Q5 vs. Q1 (Ref): 1.28 (1.08, 1.51); Q4 vs. Q1 (Ref): 1.01 (0.86, 1.18); Q3 vs. Q1 (Ref): 1.28 (1.11, 1.48); Q2 vs. Q1 (Ref): 1.14 (0.99, 1.32); p for trend=0.04; [underlined: Seafood DP]; All participants; Q5 vs. Q1 (Ref): 0.86 (0.77, 0.95); Q4 vs. Q1 (Ref): 0.91 (0.82, 1.00); Q3 vs. Q1 (Ref): 0.96 (0.87, 1.05); Q2 vs. Q1 (Ref): 1.01 (0.92, 1.10); p for trend<0.01; Pre-pregnancy BMI <18.5; Q5 vs. Q1 (Ref): 0.98 (0.56, 1.71); Q4 vs. Q1 (Ref): 1.20 (0.68, 2.12); Q3 vs. Q1 (Ref): 0.75 (0.40, 1.40); Q2 vs. Q1 (Ref): 0.89 (0.49, 1.61); p for trend=0.71; Pre-pregnancy BMI 18.5-24.9; Q5 vs. Q1 (Ref): 0.86 (0.76, 0.97); Q4 vs. Q1 (Ref): 0.94 (0.84, 1.01); Q3 vs. Q1 (Ref): 0.91 (0.81, 1.03); Q2 vs. Q1 (Ref): 0.96 (0.85, 1.01); p for trend=0.02; Pre-pregnancy BMI ≥25; Q5 vs. Q1 (Ref): 0.97 (0.82, 1.14); Q4 vs. Q1 (Ref): 0.96 (0.83, 1.11); Q3 vs. Q1 (Ref): 1.11 (0.97, 1.26); Q2 vs. Q1 (Ref): 1.10 (0.97, 1.24); p for trend=0.50; Male Fetal Sex; Q5 vs. Q1 (Ref): 0.72 (0.63, 0.82); Q4 vs. Q1 (Ref): 0.87 (0.78, 0.98) Q3 vs. Q1 (Ref): 0.95 (0.85, 1.07); Q2 vs. Q1 (Ref): 1.00 (0.89, 1.11); p for trend=0.01; Female Fetal Sex; Q5 vs. Q1 (Ref): 0.78 (0.68, 0.89); Q4 vs. Q1 (Ref): 0.81 (0.71, 0.91); Q3 vs. Q1 (Ref): 0.87 (0.77, 0.98); Q2 vs. Q1 (Ref): 0.94 (0.84, 1.06); p for trend=0.08; [underlined: Vegetable/Prudent DP]; Q5 vs. Q1 (Ref): 1.05 (0.96, 1.16); [underlined: Nordic DP]; Q5 vs. Q1 (Ref): 0.93 (0.83, 1.04); [underlined: Rice/Pasta/Poultry DP]; Q5 vs. Q1 (Ref): 1.12 (1.02, 1.24), p<0.05; [underlined: Sweets DP]; Q5 vs. Q1 (Ref): 1.05 (0.94, 1.16); [underlined: Alcohol DP]; Q5 vs. Q1 (Ref): 0.97 (0.88, 1.07); Mid Gestational Hypertension (Analytic N=47,538); Multivariable logistic regression; OR (95% CI); [underlined: Western DP]; Q5 vs. Q1 (Ref): 1.12 (0.94, 1.32); Q4 vs. Q1 (Ref): 1.05 (0.90, 1.22); Q3 vs. Q1 (Ref): 1.00 (0.86, 1.16); Q2 vs. Q1 (Ref): 1.04 (0.90, 1.20); p for trend=0.21; Late Gestational Hypertension (Analytic N=45,139); Multivariable logistic regression; OR (95% CI); [underlined: Western DP]; Q5 vs. Q1 (Ref): 1.19 (1.06, 1.34); Q4 vs. Q1 (Ref): 1.09 (0.98, 1.21); Q3 vs. Q1 (Ref): 1.18 (1.07, 1.30); Q2 vs. Q1 (Ref): 1.15 (1.04, 1.26); p for trend=0.02; Preeclampsia (Analytic N=54,778); Multivariable logistic regression; OR (95% CI); [underlined: Western DP]; All participants; Q5 vs. Q1 (Ref): 1.40 (1.11, 1.76); Q4 vs. Q1 (Ref): 1.22 (0.99, 1.50); Q3 vs. Q1 (Ref): 1.36 (1.12, 1.65); Q2 vs. Q1 (Ref): 1.15 (0.94, 1.39); p for trend=0.01; Pre-pregnancy BMI <18.5; Q5 vs. Q1 (Ref): 1.58 (0.30, 7.34); Q4 vs. Q1 (Ref): 1.20 (0.30, 4.79); Q3 vs. Q1 (Ref): 1.27 (0.34, 4.81); Q2 vs. Q1 (Ref): 0.86 (0.20, 3.73); p for trend=0.53; Pre-pregnancy BMI 18.5-24.9; Q5 vs. Q1 (Ref): 1.36 (0.97, 1.91); Q4 vs. Q1 (Ref): 1.51 (1.14, 2.02); Q3 vs. Q1 (Ref): 1.38 (1.05, 1.81); Q2 vs. Q1 (Ref): 0.19 (0.91, 1.56); p for trend=0.03; Pre-pregnancy BMI ≥25; Q5 vs. Q1 (Ref): 1.21 (0.84, 1.74); Q4 vs. Q1 (Ref): 0.81 (0.57, 1.14); Q3 vs. Q1 (Ref): 1.15 (0.84, 1.58); Q2 vs. Q1 (Ref): 1.02 (0.74, 1.41); p for trend=0.52; Male Fetal Sex; Q5 vs. Q1 (Ref): 1.10 (0.80, 1.51); Q4 vs. Q1 (Ref): 0.94 (0.70, 1.26); Q3 vs. Q1 (Ref): 1.25 (0.96, 1.64); Q2 vs. Q1 (Ref): 1.17 (0.90, 1.53); p for trend=0.98; Female Fetal Sex; Q5 vs. Q1 (Ref): 1.84 (1.32, 2.57); Q4 vs. Q1 (Ref): 1.59 (1.17, 2.15); Q3 vs. Q1 (Ref): 1.48 (1.12, 1.97); Q2 vs. Q1 (Ref): 1.10 (0.82, 1.47); p for trend<0.0001; [underlined: Seafood DP]; All participants; Q5 vs. Q1 (Ref): 0.79 (0.65, 0.97); Q4 vs. Q1 (Ref): 0.75 (0.62, 0.91); Q3 vs. Q1 (Ref): 0.85 (0.71, 1.02); Q2 vs. Q1 (Ref): 0.88 (0.74, 1.05); p for trend=0.01; Pre-pregnancy BMI <18.5; Q5 vs. Q1 (Ref): 0.40 (0.14, 1.14); Q4 vs. Q1 (Ref): 0.31 (0.09, 0.98); Q3 vs. Q1 (Ref): 0.34 (0.11, 1.07); Q2 vs. Q1 (Ref): 0.31 (0.09, 1.09); p for trend=0.19; Pre-pregnancy BMI 18.5-24.9; Q5 vs. Q1 (Ref): 0.80 (0.63–1.02); Q4 vs. Q1 (Ref): 0.82 (0.65–1.04); Q3 vs. Q1 (Ref): 0.82 (0.65–1.04); Q2 vs. Q1 (Ref): 0.78 (0.62–0.99); p for trend=0.12; Pre-pregnancy BMI ≥25; Q5 vs. Q1 (Ref): 1.21 (0.91–1.61); Q4 vs. Q1 (Ref): 1.06 (0.82–1.38); Q3 vs. Q1 (Ref): 1.07 (0.84–1.36; Q2 vs. Q1 (Ref): 1.04 (0.82–1.30); p for trend=0.27; Male Fetal Sex; Q5 vs. Q1 (Ref): 0.79 (0.62, 1.01); Q4 vs. Q1 (Ref): 0.90 (0.72, 1.14); Q3 vs. Q1 (Ref): 0.92 (0.74, 1.15); Q2 vs. Q1 (Ref): 0.97 (0.78, 1.20); p for trend=0.20; Female Fetal Sex; Q5 vs. Q1 (Ref): 0.82 (0.65, 1.05); Q4 vs. Q1 (Ref): 0.73 (0.57, 0.92); Q3 vs. Q1 (Ref): 0.79 (0.63, 0.99); Q2 vs. Q1 (Ref): 0.74 (0.59, 0.93); p for trend=0.55; [underlined: Vegetable/Prudent DP]; Q5 vs. Q1 (Ref): 1.05 (0.87, 1.27); [underlined: Nordic DP]; Q5 vs. Q1 (Ref): 0.84 (0.67, 1.05); [underlined: Rice/Pasta/Poultry DP]; Q5 vs. Q1 (Ref): 1.12 (0.93, 1.36); [underlined: Sweets DP]; Q5 vs. Q1 (Ref): 1.10 (0.90, 1.35); [underlined: Alcohol DP]; Q5 vs. Q1 (Ref): 0.88 (0.73, 1.07); Severe Preeclampsia (Analytic N=55,086); Multivariable logistic regression OR (95% CI); [underlined: Western DP]; Q5 vs. Q1 (Ref): 1.26 (0.76, 2.09); [underlined: Seafood DP]; Q5 vs. Q1 (Ref): 0.81 (0.53, 1.25); [underlined: Vegetable/Prudent DP]; Q5 vs. Q1 (Ref): 1.46 (0.94, 2.26); [underlined: Nordic DP]; Q5 vs. Q1 (Ref): 1.24 (0.76, 2.00); [underlined: Rice/Pasta/Poultry DP]; Q5 vs. Q1 (Ref): 1.00 (0.68, 1.49); [underlined: Sweets DP]; Q5 vs. Q1 (Ref): 0.92 (0.58, 1.45); [underlined: Alcohol DP]; Q5 vs. Q1 (Ref): 0.79 (0.52, 1.19) | Key confounders accounted for: Age, Physical activity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of HDP; Other covariates: TEI, Height; Funding: School of Public Health, Imperial College London; Faculty of Food Science and Nutrition, School of Health Sciences, University of Iceland; Danish Diabetes Academy, Novo Nordisk Foundation; March of Dimes Foundation; the Health Foundation; the Heart Foundation; Innovation Fund Denmark, Centre for Fetal Programming; Summary: Greater alignment with the Western DP was associated with higher risk of gestational hypertension and preeclampsia in all participants, participants with pre-pregnancy BMI 18.5-24.9, and participants with female sex fetuses, but not in participants with pre-pregnancy BMI <18.5 or ≥25 or participants with male sex fetuses. Additionally, greater alignment with the Western DP was associated with higher risk of late gestational hypertension, but not mid gestational hypertension or severe preeclampsia.; Greater alignment with the Seafood DP was associated with lower risk of gestational hypertension in all participants, participants with pre-pregnancy BMI 18.5-24.9, and participants with both male and female (trend neared significance) fetuses, but not in participants with pre-pregnancy BMI <18.5 or ≥25. Greater alignment with the seafood DP was associated with lower risk of preeclampsia in all participants, but the association was not significant in any subgroup analysis. Alignment with the Seafood DP was not associated with risk of severe preeclampsia.; Greater alignment with the Rice/Pasta/Poultry DP was associated with higher risk of gestational hypertension. No other associations between the Rice/Pasta/Poultry DP, Vegetable/Prudent DP, Nordic DP, Sweets DP, or Alcohol DP and risk of gestational hypertension, preeclampsia, or severe preeclampsia were significant.
Jarman, 2018^15^; PCS, Canada, APrON Analytic N =1,545; - Age (y): 31.4±4.2; - Race/Ethnicity (%): White: 84; Non-White: 16; - SEP:; ○ Education (%): <University: 28; University level: 72; ○ Household yearly income (%): <$100,000: 42; ≥$100,000: 58; - Pre-pregnancy BMI (%): 25-<30: 21; ≥30: 11; - Smoking (%): 1.0 | Healthy DP (continuous alignment); FFQ at: Median 17 GW; DP Description:; - Healthy DP: Higher intakes of other vegetables, green vegetables, fruit (excluding juice), orange vegetables, oils, brown pasta or rice, fish or shellfish, tomatoes, white rice or pasta; Outcome and assessment methods:; Gestational HTN assessed at: Early diagnosis <24 GW; Later diagnosis ≥24 GW; Outcomes taken from birth record. | Gestational Hypertension; Forward stepwise logistic regression OR (95% CI); 0.6 (0.4, 0.9), p=0.01 | Key confounders accounted for: Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, DM in current pregnancy; Funding: Alberta Innovates Health Solutions; Summary: Greater alignment with the Healthy DP was associated with lower risk of gestational HTN.
Miele, 2021^17^; PCS, Brazil, Preterm SAMBA; Analytic N =1,165; - Age (%): <19: 25.0; ≥35: 6.7; - Race/Ethnicity (%): Non-White: 60.3; White: 39.7; - SEP:; ○ Education (%): <12y: 67.9; ○ Yearly income (%): ≤$12,000: 73.9; ○ Employed (%): 50.2; - BMI at first visit (%): Overweight: 25.7; Obesity: 17.1; - History of HDP (%): 100% nulliparous; - Current GDM (%): 14.1 | Obesogenic DP, Intermediate DP, Vegetarian DP, & Protein DP vs. Traditional DP; 24h recall at: 19-21 GW; DP Descriptions:; - Obesogenic DP: Higher in ultra-processed and processed foods using NOVA classification (refined carbohydrate; fats; sweets); - Intermediate DP: Lower consumption of same food groups as “Obesogenic DP”; - Vegetarian DP: Higher in dairy; fruits; vegetables; - Protein DP: Higher in fatty meats; eggs; beans; very low quantity of natural foods (using NOVA classification); - Traditional DP: Higher in beans; meats; eggs; natural or minimally processed foods (using NOVA classification); Outcome and assessment methods:; PE assessed at: >20 GW; [underlined: PE]: New onset SBP ≥140mmHg or DBP ≥90mmHg w/ proteinuria and/or evidence of acute kidney injury, liver dysfunction, neurological features, hemolysis or thrombocytopenia, or fetal growth restriction | Preeclampsia; Multiple logistic regression; OR; [underlined: Obesogenic DP vs. Traditional DP (ref):] 1.82, p≥0.05; [underlined: Intermediate DP vs. Traditional DP (ref):] 1.12, p≥0.05; [underlined: Vegetarian DP vs. Traditional DP (ref):] 1.85, p≥0.05; [underlined: Protein DP vs. Traditional DP (ref):] 2.60, p<0.05 | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Parity, History of HDP,; Other covariates: Region; Funding: Brazilian National Research Council; Bill and Melinda Gates Foundation; Summary: Greater alignment with the Protein DP was associated with a higher risk of preeclampsia compared to the Traditional DP. Alignment with the Obesogenic DP, Intermediate DP, and Vegetarian DP was not associated with risk of preeclampsia when compared to the Traditional DP.
Timmermans, 2011^20^; PCS, The Netherlands, Generation R Study; Analytic N=3,187; - Age (y): Med Low: 30.2±4.6; Med Medium: 31.6±4.0; Med High: 32.4±4.0, p<0.01; Trad Low: 32.0±3.9; Trad Medium: 31.5±4.2; Trad High: 30.7±4.8, p<0.01; - Dutch ethnicity (%): 100; - SEP:; ○ Education (%): Low: Med Low: 5.0; Med High: 1.6; High: Med Low: 40.6; Med High: 74.7, p<0.01; Low: Trad Low: 0.7; Trad High: 5.3; High: Trad Low: 72.3; Trad High: 45.5, p<0.01; - Pre-pregnancy BMI: Median (IQR): Med Low: 23.0 (4.7); Med Medium: 22.1 (3.7); Med High: 21.8 (3.5), p<0.01; Trad Low: 21.9 (3.7); Trad Medium: 22.3 (3.7); Trad High: 22.7(4.6), p<0.01; ○ ≥30 (%): Med Low: 12.4; Med High: 5.3, p<0.01:; - History of DM (%): 0.0; - Smoking (%): Current: Med Low: 19.3; Med Medium: 13.6; Med High: 11.5; Previous: Med Low: 7.5; Med Medium: 7.6; Med High: 9.5, p<0.01; Current: Trad Low: 7.5; Trad Medium: 14.2; Trad High: 22.6; Previous: Trad Low: 7.5; Trad Medium: 9.0; Trad High: 8.1, p<0.01 | Mediterranean DP & Traditional DP (categorical alignment); FFQ at Median (IQR): 13.5 (3.4) GW; DP Descriptions:; - Mediterranean (Med) DP: Higher in vegetables, vegetable oils, pasta, rice, fish, and legumes, moderate intake of alcohol; Lower in sweets; - Traditional (Trad) DP: Higher in meat and potatoes; Lower in fruit, nonalcoholic drinks, fish, and bread; Outcome and assessment methods:; BP assessed at: Median (IQR): 20.5 (1.3) and 30.4 (1.1) GW; Measured by investigators. | Systolic BP; Linear regression; β (95% CI); [underlined: Mediterranean DP]; Mid pregnancy; Medium vs. High (Ref): 0.7 (–0.3, 1.6); Low vs. High (Ref): 1.3 (0.3, 2.3); Trend score: −0.5 (−0.9, −0.1); Late pregnancy; Medium vs. High (Ref): 0.7 (−0.3, 1.6); Low vs. High (Ref): 0.2 (−0.8, 1.2); Trend score: −0.1 (−0.5, 0.1); [underlined: Traditional DP]; Mid pregnancy; Medium vs. Low (Ref): 1.3 (0.4, 2.3); High vs. Low (Ref): 2.3 (1.2, 3.3); Trend score: 0.8 (0.4, 1.3); Late pregnancy; Medium vs. Low (Ref): 0.7 (−0.3, 1.6); High vs. Low (Ref): 2.6 (1.6, 3.6); Trend score: 0.9 (0.5,1.3); Diastolic BP; Linear regression β (95% CI); [underlined: Mediterranean DP]; Mid pregnancy; Medium vs. High (Ref): 0.2 (−0.6, 0.9); Low vs. High (Ref): 1.6 (0.8, 2.4); Trend score: −0.6 (−1.0, −0.3); Late pregnancy; Medium vs. High: 0.5 (−0.3, 1.2); Low vs. High (Ref): 1.0 (0.2, 1.8); Trend score: −0.3 (−0.7, −0.1); [underlined: Traditional DP]; Mid pregnancy; Medium vs. Low (Ref): 0.9 (0.1, 1.7); High vs. Low (Ref): 1.3 (0.5, 2.1); Trend score: 0.6 (0.2, 0.9); Late pregnancy; Medium vs. Low (Ref): 0.3 (−0.4, 1.1); High vs. Low (Ref): 0.8 (0.1, 1.6); Trend score: 0.3 (−0.1, 0.6) | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity; Other covariates: Gestational age, Vomiting, Folic acid use
Timmermans, 2011^20^ cont. | Outcome and assessment methods: Gestational HTN and PE at: >20 GW Retrieved from medical records.; [underlined: Gestational HTN]: SBP ≥140 mmHg and/or DBP ≥90 mmHg in previously normotensive participants on ≥2 occasions); [underlined: PE]: Gestational HTN w/ proteinuria (≥2 dipstick readings of ≥2+, 1 sample reading of ≥1+, or 24h urine collection containing ≥300 mg protein | Gestational HTN; Logistic regression; OR (95% CI); [underlined: Mediterranean DP]; Medium vs. High (Ref): 1.1 (0.8, 1.7); Low vs. High (Ref): 1.3 (0.9, 1.9); Trend score: 0.9 (0.8, 1.1); [underlined: Traditional DP]; Medium vs. Low (Ref): 1.0 (0.7, 1.6); High vs. Low (Ref): 1.3 (0.9, 1.9); Trend score: 1.1 (0.9, 1.3); Preeclampsia; Logistic regression; OR (95% CI); [underlined: Mediterranean DP]; Medium vs. High (Ref): 1.2 (0.6, 2.3); Low vs. High (Ref): 1.2 (0.6, 2.3); Trend score: 0.8 (0.6, 1.1); [underlined: Traditional DP]; Medium vs. Low (Ref): 0.7 (0.3, 1.4); High vs. Low (Ref): 1.1 (0.6, 2.1); Trend score: 1.3 (0.9, 1.7) | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity; Other covariates: Vomiting, Folic acid use; Funding: Erasmus Medical Center, Rotterdam; Erasmus University Rotterdam; Netherlands Organization for Health Research (ZonMw); Summary: Lower alignment with the Mediterranean DP was associated with higher systolic blood pressure in mid pregnancy, but not late pregnancy. Greater alignment with the Traditional DP was associated with higher systolic blood pressure in both mid and late pregnancy.; Lower alignment with the Mediterranean DP was associated with higher diastolic blood pressure in both mid and late pregnancy. Greater alignment with the Traditional DP was associated with higher diastolic blood pressure in mid pregnancy, but the trend was not significant in late pregnancy.; Lower alignment with the Mediterranean DP and greater alignment with the Traditional DP was associated with higher risk of both gestational hypertension and preeclampsia.
Torjusen, 2014^21^; PCS, Norway, MoBa; Analytic N=28,192; - Age (y): Low organic food consumption (Low): 28.6±4.3; Frequent organic food consumption (Frequent): 27.6±4.9, p<0.001; - Race/Ethnicity (%): White: >99; - SEP:; ○ Education (%): ≤12y: Low: 25.5; Frequent: 37.7, p<0.001; ≥17y: Low: 27.1; Frequent: 28.6, p<0.05; ○ High household income (%): Low: 29.7; Frequent: 23.1, p<0.001; - Pre-pregnancy BMI: Low: 23.8±4.1; Frequent: 23.3±3.9, p<0.001; - History of HTN (%): Low: 0.5; Frequent: 0.2, p<0.05; - Smoking (%): Low: 6.6; Frequent: 11.0, p<0.001 | Health and sustainability DP (tertiles of alignment); FFQ at: 20.7±3.7 GW; DP Description:; - Health and sustainability DP: High in vegetables; fruit and berries; cooking oil; olive oil; whole grain products; low in meat, including processed meat; white bread; salty snacks; Pommes frites; cakes and sweets; Outcome and assessment methods:; Preeclampsia assessed at: >20 GW; [underlined: PE:] Reported preeclampsia (>140 mmHg/90 mmHg BP w/ proteinuria >1+ dipstick on ≥2 occasions), HELLP syndrome (hemolysis, elevated liver enzymes, and low platelet count), eclampsia, early preeclampsia (<34 GW), mild preeclampsia, and severe preeclampsia on the birth notification form | Preeclampsia; Binary logistic regression; OR (95% CI); T2 vs. T1 (Ref): 0.80 (0.70, 0.91), p=0.001; T3 vs. T1 (Ref): 0.73 (0.64, 0.84), p<0.001; p for trend <0.001 | Key confounders accounted for: Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, History of HDP; Other covariates: Height, TEI, GWG; Funding: The Research Council of Norway, The Food Programme; Norwegian Ministry of Health; Norwegian Ministry of Education and Research; NIH/NIEHS; NIH/NINDS; Summary: Greater alignment with the Health and sustainability DP was associated with reduced risk of preeclampsia.

a Abbreviations: $#K: # thousands of dollars; AHA: American Heart Association; AHEI: Alternative Healthy Eating Index; AHEI-P: Alternate Healthy Eating Index for Pregnancy; aMed: alternate Mediterranean Diet; aOR: adjusted odds ratio; BIGCS: Born in Guangzhou Cohort Study; BMI: body mass index; CDGCI-PW: Chinese Dietary Guidelines Compliance Index for Pregnant Women; CI: confidence interval; DASH: Dietary Approaches to Stop Hypertension; DHA: docosahexaenoic acid; DM: diabetes mellitus; DP: dietary pattern(s); EPA: eicosapentaenoic acid; EVOO: extra virgin olive oil; FFQ: food frequency questionnaire; FPL: Federal poverty level; g: gram(s); GDM: gestational diabetes mellitus; GRMRS: Gestational Diabetes in the Mediterranean Region Study; GW: gestational weeks; GWG: gestational weight gain; h: hour(s); HDP: hypertensive disorders of pregnancy; HEI: Healthy Eating Index; HTN: hypertension; IADPSG: International Association of the Diabetes and Pregnancy Study Groups; l: liter; MDI: Mediterranean Diet Index; MDS: Mediterranean diet score; MEDAS: Mediterranean Diet Adherence Screener; MedDiet: Mediterranean diet; mmol: millimole; mo: month; NFFD: Norwegian Fit for Delivery; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Development; NIH: National Institutes of Health; NND: New Nordic Diet; NR: not reported; NS: non-significant; OR: odds ratio; PCA: principal component analysis; PCS: prospective cohort study; PUFA: polyunsaturated fatty acid; Q#: quartile; RCT: randomized controlled trial; Ref: reference; SD: standard deviation; SEP: SEP; SFA: saturated fatty acid; T#: tertile; TEI: total energy intake; TG: triglycerides; week(s); y: year(s)

Table 8 Risk of bias for randomized controlled trials examining dietary patterns consumed during pregnancy and hypertensive disorders of pregnancy^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Al Wattar, 2019^24^ | LOW | LOW | LOW | LOW | LOW | LOW
Assaf-Balut, 2017^25^ (24-28 GW) | LOW | LOW | LOW | LOW | HIGH | HIGH
Assaf-Balut, 2017^25^ (36-38 GW) | LOW | HIGH | LOW | LOW | HIGH | HIGH
Assaf-Balut, 2019^26^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Crovetto, 2021^27^ | LOW | HIGH | LOW | LOW | LOW | HIGH
Dodd, 2019^28^ | LOW | LOW | LOW | LOW | LOW | LOW
Khoury, 2005^29^ | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Melero, 2020^30^ (24-28 GW) | LOW | LOW | LOW | LOW | HIGH | HIGH
Melero, 2020^30^ (36-38 GW) | LOW | HIGH | LOW | LOW | HIGH | HIGH
Zhao, 2022^31^ (24-28 GW) | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Zhao, 2022^31^ (36-38 GW) | LOW | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898 31462531

Table 9 Risk of bias for non-randomized controlled trials examining dietary patterns consumed during pregnancy and hypertensive disorders of pregnancy^a^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Melero, 2020^30^ (24-28 GW) | SERIOUS | LOW | SERIOUS | LOW | LOW | LOW | SERIOUS | SERIOUS
Melero, 2020^30^ (36-38 GW) | SERIOUS | LOW | SERIOUS | SERIOUS | LOW | LOW | SERIOUS | SERIOUS

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 10 Risk of bias for observational studies examining dietary patterns consumed during pregnancy and hypertensive disorders or pregnancy^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Arvizu, 2020^1^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW* | SOME CONCERNS | LOW | HIGH | HIGH
Brantsaeter, 2009^2^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | HIGH | HIGH
Courtney, 2020^3^ | HIGH | LOW | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
de Seymour, 2022^4^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ding, 2021^5^ | HIGH | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Flor-Alemany, 2021^6^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Flynn, 2016^8^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Fulay, 2018^7^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hajianfar, 2018^9^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hillesund, 2014^10^ | LOW* | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | HIGH | HIGH
Hillesund, 2018^11^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hu, 2022^12^ | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | HIGH | HIGH
Ikem, 2019^13^ Gestational HTN) | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | HIGH
Ikem, 2019^13^ (PE and Severe PE) | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Jarman, 2018^15^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | HIGH | HIGH
Li, 2021^14^ | LOW | SOME CONCERNS | SOME CONCERNS | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Makarem, 2022^16^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | LOW | HIGH | HIGH
Miele, 2021^17^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Miller, 2022^18^ | HIGH | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Rifas-Shiman, 2009^19^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Timmermans, 2011^20^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Torjusen, 2014^21^ | HIGH | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | HIGH | HIGH
Wiertsema, 2021^22^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Yee, 2020^23^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool (ROBINS-E Development Group ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602 ). *Low risk of bias except for concerns about uncontrolled confounding.