# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 3 systematic reviews assessing the relationship between dietary patterns and HDP, gestational diabetes mellitus,^†^ and cardiovascular disease.^‡^ Literature search A (Appendix 4) regarding dietary patterns and HDP and gestational diabetes mellitus yielded 665 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 483 titles, 89 abstracts, and 74 full-text articles. Literature search B (Appendix 4) regarding dietary patterns and HDP and cardiovascular disease yielded 13,288 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 10,431 titles, 1,809 abstracts, and 802 full-text articles. Reasons for full-text exclusion are in Appendix 5. Six additional articles were identified from the existing systematic review^§^ and 1 additional article was identified from the manual search. The body of evidence included 31 articles:

† Andres A, Abrams SA, Byrd-Bredbenner C, . Dietary Patterns Consumed During Pregnancy and Risk of Gestational Diabetes Mellitus: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR07

‡ Anderson CAM, Gardner C, Talegawkar S, . Dietary Patterns and Risk of Cardiovascular Disease: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR13

§ Raghavan R, Dreibelbis C, Kingshipp BJ, . Dietary Patterns before and during Pregnancy and Risk of Hypertensive Disorders of Pregnancy: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0101

Figure 2 Literature search and screen flowchart

Literature search A in PubMed, Embase, Cochrane, and CINAHL, yielded 665 search results after the removal of duplicates. Dual-screening resulted in the exclusion of 483 titles, 89 abstracts, and 74 full-text articles. Nine articles were ultimately included from search A. Literature search B in PubMed, Embase, Cochrane, and CINAHL, yielded 13,288 search results after the removal of duplicates. Dual-screening resulted in the exclusion of 10,431 titles, 1,809 abstracts, and 802 full-text articles. 15 articles were included from search B. Six additional articles were identified from the existing systematic review and 1 additional article was identified from the manual search. The body of evidence included 31 articles.

## Description of the evidence

This systematic review included 31 articles from 22 studies, including 23 articles from 16 prospective cohort studies (PCS),^1–23^ 8 articles from 6 randomized controlled trials (RCT),^24–31^ and 1 article from 1 non-randomized controlled trial (NRCT),^30^ that address the relationship between dietary patterns during pregnancy and risk of hypertensive disorders of pregnancy (see Table 7). Articles were from countries classified as high or very high on the Human Development Index^*^, published between January 1980 and May 2023, and enrolled participants during pregnancy who were generally healthy, including those with overweight and obesity.

* The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

The analytic sample size for RCT and NRCT ranged from 260^30^ to 1,137,^24^ with most of the trials including at least 500 participants.^24–28,^ ^31^ For PCS, the analytic sample size ranged from 55^18^ to 72,072,^10^ but most had approximately 1,000 or more.^1,^ ^2,^ ^4,^ ^5,^ ^7,^ ^8,^ ^10,^ ^12–17,^ ^19–23^

Six articles from 4 studies were conducted in the U.S.,^7,^ ^14,^ ^16,^ ^18,^ ^19,^ ^23^ 4 studies were conducted in China,^4,^ ^5,^ ^12,^ ^31^ and 5 articles from 3 studies each were conducted in Norway^2,^ ^10,^ ^11,^ ^21,^ ^29^ and Spain.^6,^ ^25–27,^ ^30^ Two studies were conducted in the U.K.^8,^ ^24^ and 2 articles from 1 study each were conducted in Denmark^1,^ ^13^ and the Netherlands.^20,^ ^22^ One study each was conducted in Australia,^28^ Ireland,^3^ Iran,^9^ Canada,^15^ and Brazil.^17^

### Participant characteristics

#### Age

Twenty-six articles reported the mean or median age of participants, which ranged from 27 to 33 years in the majority of articles.^1,^ ^3–8,^ ^10,^ ^11,^ ^13–16,^ ^18–26,^ ^28–31^ The median age of participants in 1 RCT was 37 years.^27^ Five articles reported approximately 16%,^12^ 12%,^10^ 10%,^16^ and 7%,^11,^ ^17^ of participants were ≥35 years and in 2 articles, approximately 4%^24^ and 1%^2^ of participants were ≥40 years. One article included approximately 25% of participants ≤19 years^17^ and 2 more included some participants ≤20 years.^2,^ ^23^ One article reported including participants ranging from 20 to 40 years old.^9^ Four articles excluded participants ≤18 years^5,^ ^11,^ ^14,^ ^31^ and an additional article excluded participants ≤16 years.^24^

#### Health status

##### Pre-pregnancy BMI

All articles reported pre-pregnancy or early pregnancy (first trimester or early second trimester) BMI. Twenty-five articles enrolled participants predominantly without overweight or obesity, that is, with pre-pregnancy or early pregnancy BMI <25 kg/m^2^,^1,^ ^2,^ ^6,^ ^7,^ ^9–11,^ ^13–15,^ ^17,^ ^19–22,^ ^25–30^ <24 kg/m^2^ (using Chinese Obesity Working Group ethnicity-specific cutoffs^†^),^12,^ ^14,^ ^31^ or <23 kg/m^2^ (using World Health Organization ethnicity-specific cutoffs^‡^).^4,^ ^5^

† Zhou BF. Predictive values of body mass index and waist circumference for risk factors of certain related diseases in Chinese adults--study on optimal cut-off points of body mass index and waist circumference in Chinese adults. BES. 2002 Mar 1;15(1):83–96 12046553 .

‡ WHO Expert Consultation. Appropriate body-mass index for Asian populations and its implications for policy and intervention strategies. The Lancet. 2004;363(9403):157–163. doi: 10.1016/S0140-6736(03)15268-3

Six articles enrolled participants exclusively^8^ or predominantly^3,^ ^16,^ ^18,^ ^23,^ ^24^ with pre-pregnancy or early pregnancy BMI ≥30 kg/m2 8, 24 or ≥25 kg/m2. ^3,^ ^16,^ ^18,^ ^23^

##### History of HDP

Half of articles did not report on history of any type of hypertension.^3,^ ^5,^ ^6,^ ^9–11,^ ^15,^ ^19,^ ^20,^ ^25,^ ^26,^ ^28–31^ Five articles enrolled 0.3-6% of participants with a history of hypertension^7,^ ^12,^ ^13^ or preeclampsia.^24,^ ^27^ Eight articles exclusively enrolled nulliparous participants^2,^ ^16,^ ^17,^ ^21,^ ^23^ or excluded participants with a history of HDP^1^ or preeclampsia.^14,^ ^18^ One article excluded participants with a previous pregnancy complication resulting in delivery <32 gestational weeks (GW).^4^ Two articles excluded participants with hypertension before enrollment.^8,^ ^22^

##### Diabetes in current pregnancy

Five articles did not report diabetes prevalence during pregnancy^1,^ ^2,^ ^5,^ ^9,^ ^28^ Seven articles excluded those with pre-existing diabetes^3,^ ^7,^ ^8,^ ^11,^ ^14,^ ^18,^ ^24^ and 3 articles reported approximately 1-5% of participants had pre-existing diabetes.^10,^ ^23,^ ^27^ Fifteen articles reported approximately 1-17% of participants had gestational diabetes mellitus (GDM) in the current pregnancy and 4 articles reported GDM prevalence in the current pregnancy was ≥20%.^4,^ ^8,^ ^12,^ ^25^ One RCT excluded participants with GDM in the current pregnancy.^26^ Two articles reported baseline fasting blood glucose (FBG) levels: 1 RCT exclusively enrolled those with FBG <92 mg/dL^31^ at 8-12 GW and 1 article reported that mean FBG was approximately 77 mg/dL^6^ at 16 GW. One article reported 10.5% of participants had diabetes (pre-existing or GDM) in the current pregnancy.^22^ One article reported 0.2% of participants had a history of diabetes, but did not specify the type of diabetes.^12^ One article excluded those with a history of diabetes (not specified)^20^ or with high-risk pregnancies caused by unspecified diabetes.^29^

#### Race and/or ethnicity

Seven articles did not report race and/or ethnicity,^1,^ ^5,^ ^6,^ ^9,^ ^13,^ ^29,^ ^31^ although 2 of the articles were conducted in China.^5,^ ^31^

##### White

Half of articles reported the majority of participants were White,^2,^ ^3,^ ^7,^ ^8,^ ^10,^ ^11,^ ^15,^ ^16,^ ^19,^ ^21,^ ^23,^ ^25–28^ of which 4 articles reported >90% White participants.^2,^ ^3,^ ^10,^ ^21^ Another 4 articles reported approximately 10-40% of participants were White.^14,^ ^17,^ ^18,^ ^24^

##### Asian & Pacific Islander

Seven articles reported approximately 1-44% of participants were Asian,^7,^ ^8,^ ^16,^ ^23,^ ^24,^ ^27,^ ^28^ with 1 trial additionally specifying approximately 8% of participants were of South Asian ethnicity.^28^ One article reported approximately 20% of participants were Asian American or Pacific Islander.^14^ Two articles reported 83-98% participants were of Han ethnicity^4,^ ^12^ and an additional article reported approximately 24% Native Hawaiian, 24% Filipino, and 22% Japanese participants.^18^

##### Hispanic

Seven articles reported approximately 6-30% Hispanic ethnicity participants.^7,^ ^14,^ ^16,^ ^23,^ ^25–27^ In one additional trial, all participants were Hispanic.^30^

##### Black

Seven articles reported approximately 2-24% of participants were Black.^7,^ ^8,^ ^16,^ ^19,^ ^23,^ ^24,^ ^27^ Another article reported approximately 30% of participants were Black.^14^

##### Other

One article conducted in Brazil reported that most participants were not White,^17^ but provided no additional information about participant race and/or ethnicity. Two articles reported that participants were exclusively of Dutch ethnicity.^20,^ ^22^ No articles reported American Indian or Alaska Native participants.

#### SEP

##### Education

Five articles did not report participant education level.^13,^ ^18,^ ^24,^ ^27,^ ^28^ In most articles that did report education data, the majority of participants had at least some higher education or were described as having “high” or “higher” education.^2–6,^ ^8,^ ^10–12,^ ^14–16,^ ^19–23,^ ^25,^ ^26,^ ^29^ Six articles reported that the majority of participants had a high school education or less.^1,^ ^7,^ ^9,^ ^17,^ ^30,^ ^31^

##### Income, Occupation, or Other

Half of the articles did not report on income, occupation, or another measure of SEP. Of the 10 articles that reported income, 8 stated that a majority of participants had at least a “middle” income according to income level cutoffs specific to each country.^4,^ ^5,^ ^7,^ ^11,^ ^12,^ ^15,^ ^17,^ ^19^ One article only reported that approximately 30% of participants had “high” income.^21^ Another article reported approximately 23% of participants earned an income below 200% of the U.S. Federal poverty level.^23^

Of the 5 articles that reported occupation, 4 described participants as mostly employed^11,^ ^17,^ ^25,^ ^26^ and 1 described participants as mostly unemployed.^30^

Six articles reported a SEP measure other than education, income or occupation.^8,^ ^9,^ ^13,^ ^23,^ ^27,^ ^28^ One article from Australia noted that approximately 17% of the participants were classified as most disadvantaged based on the Socio-economic Index for Areas—Index of Relative Socio-economic Disadvantage.^28^ One U.S. article reported approximately 26% of participants had public insurance.^23^ In an article from the U.K., 43% of participants were classified as “most deprived” on an index of multiple deprivation.^8^ One article stated the majority of participants were classified as “high” SES^27^; 2 additional articles reported the majority of participants were classified as “moderate” SES or above, with approximately one-quarter of participants classified as “high” SES.^9,^ ^13^

#### Smoking

One-fourth of the articles did not describe smoking status of participants.^4,^ ^5,^ ^8,^ ^9,^ ^17–19,^ ^24^ A range of approximately 1-11% of participants smoked during pregnancy in 15 articles^2,^ ^3,^ ^6,^ ^7,^ ^10–12,^ ^15,^ ^21,^ ^25–28,^ ^30,^ ^31^ and an additional 3 articles conducted in the Netherlands^20,^ ^22^ and Denmark^13^ reported 15-25% of participants smoked during pregnancy. Two articles stated approximately 8-25% of participants had ever smoked or smoked before pregnancy^1,^ ^20^ and 3 articles conducted in Spain^6^ and the U.S.^16^ reported approximately 40% of participants had ever smoked or smoked before pregnancy. Two articles excluded participants who smoked,^14,^ ^29^ although one of them only excluded participants who smoked if their pre-pregnancy BMI was <30 kg/m^2^.^14^

### Intervention/exposures and comparators

Dietary pattern (DP) was defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they were habitually consumed.

Dietary patterns were assessed using experimental diets in 8 articles from 6 RCT and 1 NRCT,^24–31^ index/score analysis in 13 articles,^1,^ ^3,^ ^5–7,^ ^10,^ ^11,^ ^14,^ ^16,^ ^18,^ ^19,^ ^22,^ ^23^ and factor/cluster analysis in 10 articles.^2,^ ^4,^ ^8,^ ^9,^ ^12,^ ^13,^ ^15,^ ^17,^ ^20,^ ^21^ The dietary pattern components are detailed in Table 5 and visualized in Appendix 6.

Table 5 Dietary Pattern Components^*^ * Abbreviations: DASH: Dietary Approaches to Stop Hypertension; DHA: docosahexaenoic acid; DP: dietary pattern; EPA: eicosapentaenoic acid; EVOO: extra virgin olive oil; FFQ: food frequency questionnaire; MUFA: monounsaturated fatty acids; PUFA: polyunsaturated fatty acids; SFA: saturated fatty acids; SSB: sugar-sweetened beverages; TFD: Three-day food diary

Reference | Dietary pattern | Dietary pattern components
Experimental Diet
Al Wattar, 2019^24^ | Mediterranean-style supplemented w/ mixed nuts and EVOO | Positive: Olive oil (as main fat and svg/d); Nuts (including peanuts) Vegetables; Fruit (including juice); Pulses; Fish or shellfish; White meat over red meat; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial sweets or pastries
Assaf-Balut, 2017^25^; Assaf-Balut, 2019^26^ | Mediterranean-style supplemented w/ pistachios and EVOO | Positive: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries
Crovetto, 2021^27^ | Mediterranean-style supplemented w/ walnuts and EVOO | Positive: EVOO; walnuts; vegetables; fresh fruit; dairy products; whole grains; sofrito; legumes; fish; fatty fish; white meat; Negative: Refined grains; red meat; processed meat; soda drinks; commercial bakery foods, sweets, and pastries; butter, margarine, or cream
Dodd, 2019^28^ | Healthy Eating Index | Positive: Vegetables; fruit; dairy
Khoury, 2005^29^ | Cholesterol-lowering | Higher in fish and fish products, including fatty fish; rapeseed-based margarine; oils, including olive oil and rapeseed oil; nuts, olives, and seeds; vegetables; and fruits; Lower in fatty milk; meat and meat products; fatty minced meat; butter; and hard margarines
Melero, 2020^30^ | Mediterranean-style supplemented w/ pistachios and EVOO | Positive: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; Negative: commercial pastries; red meat or sausages; animal fat; sugar-sweetened beverages; Alcohol and fruit (including juice) components excluded
Zhao, 2022^31^ | Mediterranean-style w/ recommended additional pistachios and EVOO | Positive: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries
Index/Score Analysis
Arvizu, 2020^1^ | American Heart; Association; Primary | Positive: Fruits and vegetables; Whole grains; Fish and shellfish; Negative: SSB; Sodium
Arvizu, 2020 cont. | American Heart; Association; Secondary | Positive: Fruits and vegetables; Whole grains; Fish and shellfish; Nuts, seeds, and legumes; Negative: SSB; Sodium; Processed meat; Saturated fat
Arvizu, 2020 cont. | DASH | Positive: Fruits and juices; Vegetables; Nuts/legumes; Whole grains; Low-fat dairy; Negative: Red/processed meat; SSB; Sodium
Courtney, 2020^3^ | Modified DASH | Positive: fruit and fruit juice; vegetables (excluding potatoes); whole grains; nuts/seeds/legumes; low-fat dairy; Negative: red lean/red processed meat; SSB, sweet snacks, and desserts; sodium; salty snacks
Ding, 2021^5^ | Chinese Dietary Guidelines Compliance Index for Pregnant Women | Positive: staple foods (cereals and their products, potatoes, and beans other than soybeans); green leafy and colored vegetables (red and yellow); milk and its products (milk, yogurt, formula milk powder); soybean and its products; nuts; lean meat (livestock and poultry meat); animal blood and liver; iodized table salt, iodine-rich seafood; Negative: pickled food, fried food, cream cake, chocolate, other high-salt, high-oil, and high-sugar food
Flor-Alemany, 2021^6^ | Mediterranean Diet Score | Positive: Vegetables; Potatoes; Legumes; Fruits; Whole Grains; Fish; Olive Oil; Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol component excluded
Fulay, 2018^7^ | DASH | Positive: fruit (including fruit juice); vegetables (not potatoes); whole grains; nuts/legumes; low-fat dairy; Negative: sodium; SSB; red and/or processed meats
Fulay, 2018^7^ | DASH OMNI | Positive: fruit (including fruit juice); vegetables (not potatoes); whole grains; nuts/legumes; low-fat dairy; MUFA and PUFA; Negative: sodium; SSB; red and/or processed meats
Hillesund, 2014^10^ | New Nordic Diet | Positive: meal frequency; Nordic fruits (apples, pears, plums, and strawberries); root vegetables; cabbages; potatoes:total potatoes, rice, or pasta; whole grain bread over refined bread; oatmeal; foods from the wild countryside (wild fish, seafood, game, and wild berries); milk over juice; water:SSB
Hillesund, 2018^11^ | Norwegian Fit for Delivery | Positive: regular meals; drinking water when thirsty; vegetables w/ dinner; fruits and vegetables btw meals; reading nutrition labels before buying; Negative: sweets and snacks without appreciation; large portion sizes of unhealthy foods; added sugar; salt; eating beyond satiety
Li, 2021^14^ | Alternative Healthy Eating Index | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA; Negative: Red and Processed Meat; SSB and Fruit Juice; Sodium; Alcohol and trans-fat components excluded
Li, 2021^14^ | Alternate Mediterranean Diet | Positive: Vegetables; Fruit; Nuts; Fish; Lean Meat (poultry, lean beef); Negative: Red and Processed Meat; Sodium.; Neutral: Grains and Starches; Dairy Foods; Alcohol component excluded
Li, 2021^14^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Makarem, 2022^16^ | Alternate Mediterranean Diet | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA:SFA; Negative: Red and Processed Meat; Moderate: Alcohol
Miller, 2022^18^ | Healthy Eating Index-2015 | Positive: Total vegetables; Greens and beans; Total fruit; Whole fruit; Fish; Whole grains; Total protein foods; Dairy; PUFA+MUFA:SFA; Negative: Refined grains; Calories from solid fat, added sugars, and alcohol; Sodium
Miller, 2022^18^ | Alternate Mediterranean Diet | Positive: Vegetables (excluding potatoes); Total fruit; Nuts; Legumes; Fish; Whole grains; MUFA:SFA; Negative: Red and processed meat; Moderate: Alcohol
Miller, 2022^18^ | Modified DASH | Positive: Vegetables (excluding potatoes); Fruit; Nuts, seeds, and legumes; Fish; Whole grains; Low-fat dairy; Negative: Red and processed meat; SSB and fruit juice; Sodium
Rifas-Shiman, 2009^19^ | Alternative Healthy Eating Index for Pregnancy | Positive: vegetables, fruit, white meat (poultry or fish):red meat, fiber, PUFA:SFA, and folate, calcium, and iron from foods; Negative: trans fat
Wiertsema, 2021^22^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy.; Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Yee, 2020^23^ | Healthy Eating Index-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit (including juice); Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids; Negative: Refined Grains; Empty Calories (i.e., energy from solid fats, alcohol, and added sugars); Sodium
Factor/Cluster Analysis
Brantsæter, 2009^2^ | Vegetable | Higher intake of vegetables, cooking oil, olive oil, fruits and berries, rice, and chicken
Brantsæter, 2009^2^ | Processed food | Higher intake of processed meat products, white bread, French fries, salty snacks, and sugar-sweetened drinks and high negative loadings on oily fish, high-fiber breakfast cereals, and lean fish
Brantsæter, 2009^2^ | Potato and fish | Higher intake of cooked potatoes, processed fish, lean fish, meat spread, fish spread and shellfish, and margarine
Brantsæter, 2009^2^ | Cakes and sweets | Higher intake of cakes, waffles and pancakes, buns, ice cream, sweet biscuits, sweets, and chocolate
de Seymour, 2022^4^ | Fish, poultry and vegetables-based | Higher intake of fish; poultry; legumes and bean products; green leafy vegetables; root vegetables; other vegetables; seafood; fruits; eggs; organ meats; beverages; bread; dairy; soup; nuts
de Seymour, 2022^4^ | Pasta, sweetened beverages, oils and condiments-based | Higher intake of pasta; sweetened beverages; oils and condiments; fast food
Flynn, 2016^8^ | Fruit & Veg | Higher intake of bananas; citrus fruit; dried fruit; fresh fruit; green vegetables; pulses; root vegetables; salad vegetables; tropical fruit; yoghurt
Flynn, 2016^8^ | African/Caribbean | Higher intake of red meat; cassava; white meat; rice including pilau, fried or jollof rice; plantain; fish
Flynn, 2016^8^ | Processed | Higher intake of chocolate; crisps; green vegetables; potatoes; processed meat and meat products; root vegetables; squash and fizzy drinks; sugar free squash and fizzy drinks; chips
Flynn, 2016^8^ | Snacks | Higher intake of biscuits and cookies; cakes and pastries; chocolate; full fat cheese; sweets
Hajianfar, 2018^9^ | Healthy | Higher intake of green vegetables, leafy vegetables, colored vegetables, fruits, low fat dairy, poultry, bulky vegetables, red meat, citrus, nuts, fish, olive, marinades, sweet fruit, egg, and unsaturated fat
Hajianfar, 2018^9^ | Western | Higher intake of processed meats, fruits, fruits juice, citrus, nuts, fish, desserts and sweets, sugar, saturated fat, sweet fruit (melon, persimmon, date, fig, grapes, raisins, berries that have high glycemic index), potato, legumes, coffee, egg, pizza, high fat dairy, whole grain, and soft drinks
Hajianfar, 2018^9^ | Traditional | Higher intake of refined grains, colored vegetables, olive, sugar, salt, spices, unsaturated fat, garlic, onion, and tea
Hu, 2022^12^ | Traditional-TFD | Higher intake of tubers; vegetables; fruits; red meat; coarse cereals; rice; nuts
Hu, 2022^12^ | Wheaten food-coarse cereals-TFD | Higher intake of wheat flour and products; coarse cereals; beans and bean products; lower intake of eggs; rice
Hu, 2022^12^ | Sweet food-seafood-TFD | Higher intake of pastries and candies; sweet beverages; shrimps, crabs, and mussels; fruits
Hu, 2022^12^ | Fried food-protein-rich-TFD | Higher intake of fried foods; beans and bean products; dairy products
Hu, 2022^12^ | Fish-seafood-FFQ | Higher intake of shrimps, crabs and mussels; marine fish; freshwater fish; organ meat; seaweed; poultry
Hu, 2022^12^ | Protein-rich-FFQ | Higher intake of dairy products; milk; eggs; beans and bean products; nuts; pastries and candies
Hu, 2022^12^ | Vegetable-fruit-rice-FFQ | Higher intake of vegetables; fruits; rice; nuts
Ikem, 2019^13^ | Western | Higher intake of pork; beef and veal; mixed meat; cold meat; egg; potatoes; French fries; dressing sauce; white bread; cold fish; butter; margarine
Ikem, 2019^13^ | Vegetable/Prudent | Higher intake of legumes; root vegetables; tomato; salad; corn; mushroom; onion; cabbage; other vegetables; other fruit
Ikem, 2019^13^ | Seafood | Higher intake of lean fish; oily fish; shellfish; cold fish; smoked fish; oil; beef and veal; lamb; egg; onion; tomato; Asian vegetables; other vegetables; fermented milk; yogurt
Ikem, 2019^13^ | Nordic | Higher intake of dark bread; Nordic fruit; hard cheese; banana; dried fruit; sweet spread; cold meat
Ikem, 2019^13^ | Rice/Pasta/Poultry | Higher intake of rice; pasta; poultry
Ikem, 2019^13^ | Sweets | Higher intake of chocolate; dairy dessert; candy; sweet spread; sugar cakes; white bread; margarine; snacks; French fries
Ikem, 2019^13^ | Alcohol | Higher intake of liquor; wine; beer; soybean; root vegetables; berries
Jarman, 2018^15^ | Healthy | Higher intake of other vegetables, green vegetables, fruit (excluding juice), orange vegetables, oils, brown pasta or rice, fish or shellfish, tomatoes, white rice or pasta
Miele, 2021^17^ | Obesogenic | Higher intake of ultra-processed and processed foods using NOVA classification (refined carbohydrate; fats; sweets)
Miele, 2021^17^ | Intermediate | Lower intake of same food groups as “Obesogenic DP”
Miele, 2021^17^ | Vegetarian | Higher intake of dairy; fruits; vegetables
Miele, 2021^17^ | Protein | Higher intake of fatty meats; eggs; beans; very low intake of natural foods (using NOVA classification)
Miele, 2021^17^ | Traditional | Higher intake of beans; meats; eggs; natural or minimally processed foods (using NOVA classification)
Timmermans, 2011^20^ | Mediterranean | Higher intake of vegetables, vegetable oils, pasta, rice, fish, and legumes, moderate intake of alcohol; Lower intake of sweets
Timmermans, 2011^20^ | Traditional | Higher intake of meat and potatoes; Lower intake of fruit, nonalcoholic drinks, fish, and bread
Torjusen, 2014^21^ | Health and sustainability | Higher intake of vegetables; fruit and berries; cooking oil; olive oil; whole grain products; lower intake of meat, including processed meat; white bread; salty snacks; Pommes frites; cakes and sweets

### Timing of exposure assessment

Approximately one-third of articles assessed diet during the first trimester of pregnancy,^4,^ ^7,^ ^9,^ ^14,^ ^16,^ ^19,^ ^20,^ ^22,^ ^23^ with one of the articles assessing diet during the first and second trimester.^14^ Approximately half of articles assessed diet during the second trimester,^1,^ ^2,^ ^5,^ ^6,^ ^8,^ ^10–13,^ ^15,^ ^17,^ ^21,^ ^24,^ ^27,^ ^29^ with 2 of the articles assessing diet during the second and third trimester.^27,^ ^29^ The remaining articles assessed diet during all three trimesters.^3,^ ^18,^ ^25,^ ^26,^ ^28,^ ^30,^ ^31^

### Outcome

Outcomes varied across included articles, and outcome definitions were reported with varying levels of detail.

#### Preeclampsia and/or Eclampsia

Twenty-two articles reported preeclampsia and/or eclampsia as outcome(s).^1,^ ^2,^ ^4,^ ^8–11,^ ^13,^ ^14,^ ^17,^ ^19–22,^ ^24–28,^ ^30,^ ^31^ One article additionally reported risk of early preeclampsia,^10^ 2 additionally reported risk of severe preeclampsia,^1,^ ^13^ and another article additionally reported risk of severe preeclampsia/HELLP/eclampsia combined.^11^ One RCT reported HELLP (Hemolysis, Elevated Liver enzymes and Low Platelets) syndrome as an outcome.^27^

Approximately one-third of the preeclampsia articles reported ≥4% preeclampsia incidence^2,^ ^11,^ ^16,^ ^17,^ ^21,^ ^24,^ ^27^; of those, 3 articles reported ≥7% preeclampsia incidence.^16,^ ^17,^ ^27^

#### Gestational Hypertension

Fifteen articles reported gestational hypertension as an outcome.^1,^ ^5,^ ^12–16,^ ^20,^ ^22,^ ^25–28,^ ^30,^ ^31^ One article additionally reported the risk of mid- and late- pregnancy gestational hypertension.^13^ Three of these articles reported ≥14% gestational hypertension incidence.^12,^ ^13,^ ^16^

#### Blood Pressure

Twelve articles reported blood pressure as an outcome.^3,^ ^6,^ ^7,^ ^9,^ ^12,^ ^20,^ ^22,^ ^25–27,^ ^30,^ ^31^ Eleven reported systolic and diastolic blood pressure,^3,^ ^6,^ ^7,^ ^9,^ ^12,^ ^20,^ ^22,^ ^25,^ ^26,^ ^30,^ ^31^ while 3 reported mean blood pressure.^3,^ ^12,^ ^27^

#### Hypertensive Disorders of Pregnancy

Five articles reported risk of any hypertensive disorder of pregnancy (gestational hypertension, preeclampsia, and/or eclampsia) as a composite outcome.^7,^ ^18,^ ^22,^ ^23,^ ^29^ Two of these articles reported ≥22% HDP incidence.^18,^ ^23^

#### Proteinuria

Three articles reported proteinuria as an outcome.^25,^ ^26,^ ^30^

## Synthesis of the evidence

Twenty-three dietary patterns from 18 articles (17 unique trials or cohorts) were statistically significantly associated with lower risk of HDP^2,^ ^5,^ ^9–16,^ ^18,^ ^21,^ ^27,^ ^30^ and/or lower blood pressure.^3,^ ^6,^ ^12,^ ^20,^ ^22^ Six dietary patterns from 5 articles were statistically significantly associated with higher risk of HDP ^2,^ ^9,^ ^13^ or higher blood pressure.^20,^ ^27^ Thirty-seven dietary patterns from 19 articles (15 unique trials or cohorts) showed no statistically significant association with any outcomes.^1,^ ^2,^ ^4,^ ^7–9,^ ^12,^ ^13,^ ^17–19,^ ^23–26,^ ^28–31^

A summary of the findings is below. Please refer to Table 7 for more details and Appendix 6 for a visualization of the dietary pattern components.

### Intervention studies

Seven articles from 5 trials reported no statistically significant effect of a dietary pattern on risk of HDP.^24–26,^ ^28–31^ The multicenter, U.K.-based ESTEEM RCT randomized participants with metabolic risk factors to a Mediterranean-style diet supplemented with mixed nuts and extra virgin olive oil (EVOO) (provided by investigators) or usual care.^24^ The intervention did not have a statistically significant effect on risk of preeclampsia compared to usual care in all participants and in subgroup analyses by baseline BMI, baseline triglycerides, and chronic hypertension status.

The St. Carlos GDM Prevention Study RCT conducted in Spain also included a Mediterranean-style diet supplemented with nuts and EVOO (provided by investigators) intervention, which was compared to a Mediterranean-style diet with restricted fat.^25^ The intervention had no effect on systolic or diastolic blood pressure at either 24-28 or 36-38 GW, gestational hypertension, preeclampsia, or proteinuria. Two secondary analyses of the St. Carlos GDM Prevention Study that restricted the analysis to normoglycemic participants only^26^ or Hispanic participants only^30^, respectively, also found that the intervention had no statistically significant effect on systolic or diastolic blood pressure at either 24-28 or 36-38 GW, gestational hypertension, preeclampsia, or proteinuria.

Zhao et al. also conducted an RCT that examined a Mediterranean-style diet intervention in China.^31^ The intervention group was also encouraged to consume EVOO and roasted pistachios every day (but was not supplied with EVOO or nuts), while the control group was recommended to restrict dietary fat. The intervention had no effect on blood pressure at 24-28 GW or 36-38 GW, gestational hypertension, or preeclampsia.

The OPTIMISE trial was conducted in Australia,^28^ where participants were randomized to a lifestyle intervention including dietary advice consistent with the Australian dietary standards or standard care. Participants in the intervention group were specifically advised to increase their intake of fiber and to consume 2 servings of fruit, 5 servings of vegetables, and 3 servings of dairy per day. The intervention had no effect on risk of gestational hypertension or preeclampsia, although the differences in healthy eating index scores between groups at follow-up were very small (approximately 2 points at 28 GW and 36 GW), which may indicate a deviation from the intended intervention.

The CARRDIP trial conducted in Norway^29^ implemented a cholesterol-lowering diet encouraging the intervention group to consume fatty fish, vegetable oils, nuts and nut butters, margarine based on olive- or rapeseed oil, and avocado to replace meat, butter, cream, and fatty dairy products; fresh fruits and vegetables; skimmed or low-fat dairy products in place of full fat products; legumes, vegetable main dishes, fatty fish, or poultry with the fat trimmed for a main meal most days. The control group participants were advised to consume a usual diet based on Norwegian foodstuffs and asked not to introduce more oils or low-fat meat and dairy products than usual. The intervention did not have a statistically significant effect on risk of hypertensive disorders of pregnancy.

Two trials reported statistically significant effects on risk of HDP or blood pressure.^27,^ ^30^

The secondary analysis of the St. Carlos GDM Prevention Study authored by Melero et al.^30^ also compared outcomes to a non-randomized group, where the intervention was implemented in a “real world” setting, to the original trial control group. In this “real world” group, participants were recommended to consume EVOO and nuts, but were not provided with these foods. The “real world” intervention was associated with lower incidence of proteinuria but did not have an effect on systolic or diastolic blood pressure at 24-28 GW or 36-38 GW, gestational hypertension, or preeclampsia.

The Spanish IMPACT BCN trial^27^ randomized intervention group participants to a Mediterranean-style diet supplemented with walnuts and EVOO and control group participants to usual care. Participants in the intervention group had higher mean blood pressure at follow-up compared to the control group. There were no statistically significant differences in risk of preeclampsia or incidence of gestational hypertension, eclampsia, or HELLP syndrome between groups.

### Observational studies

#### Studies that suggest an association between dietary patterns and lower risk of HDP

Dietary patterns based on the following indices/scores were statistically significantly associated with lower risk of HDP and/or lower blood pressure: DASH and its variations,^3,^ ^14,^ ^18,^ ^22^ Mediterranean Diet Score and its variations,^6,^ ^16^ Healthy Eating Indices,^14,^ ^18^ New Nordic Diet,^10^ Norwegian Fit for Delivery diet,^11^ and the Chinese Dietary Guidelines Compliance Index for Pregnant Women (CDGCI-PW).^5^ Dietary patterns based on the following indices/scores may suggest a beneficial association with risk of HDP and/or blood pressure, despite a lack of statistically significant results: Healthy Eating Indices,^19,^ ^23^ DASH,^22^ and alternate Mediterranean Diet.^18^ However, some of these results had small magnitudes of effect.^19,^ ^22^ These patterns were generally characterized by higher intakes of vegetables, fruits, whole grains, legumes, and nuts and seeds, and lower intakes of red and processed meat, added sugars, and sodium.

The following dietary patterns derived via factor or cluster analysis were statistically significantly associated with lower risk of HDP and/or lower blood pressure: ‘Western’ DP,^9^ ‘Healthy’ DP,^9,^ ^15^ ‘Mediterranean’ DP,^20^ ‘Health and sustainability’ DP,^21^ ‘Vegetable’ DP,^2^ ‘Seafood’ DP,^13^ ‘Fish-seafood-FFQ’ DP,^12^ and a ‘Sweet food-seafood-TFD’ DP.^12^ The following dietary patterns derived via factor or cluster analysis suggested a beneficial association with risk of HDP and/or blood pressure, despite a lack of statistically significant results: ‘Cakes and sweets’ DP,^2^ ‘Pasta, sweetened beverages, oils and condiments-based’ DP,^4^ ‘Fruit & Veg’ DP,^8^ ‘Wheaten food-coarse cereals-TFD’ DP,^12^ ‘Vegetable-fruit-rice-FFQ’ DP,^12^ ‘Sweets’ DP.^13^ These patterns were generally characterized by higher intakes of vegetables, fruits, fish, and unsaturated fats. There were few other consistencies among the dietary patterns.

Results and methods of interest from these articles are included below and in Table 7.

Three articles were secondary analyses of an RCT.^3,^ ^6,^ ^11^ The secondary analysis of the Irish ROLO trial found that greater alignment with DASH was associated with lower third trimester (but not second trimester) diastolic blood pressure and mean arterial pressure; however, it was not associated with systolic blood pressure.^3^ The secondary analysis from the Spanish GESTAFIT trial^6^ reported that greater alignment with the MedDietScore at 16 GW was associated with lower systolic and diastolic blood pressure at 34 GW. In a secondary analysis of the Norwegian Fit for Delivery (NFFD) trial,^11^ when additionally controlling for physical activity, greater alignment with the NFFD diet score in early pregnancy was statistically significantly associated with a reduced risk of total preeclampsia, and was nearly significantly associated with a reduced risk of severe preeclampsia/HELLP/eclampsia. When confined to the control group from the original trial, findings for risk of total preeclampsia were no longer statistically significant.

Three articles reported a stronger association between DP and risk of HDP among some groups at higher risk compared to participants at lower risk for HDP, although results were not consistent.^10,^ ^12,^ ^13^ One article from the Norwegian MoBa cohort^10^ reported that greater alignment with the New Nordic Diet was associated with reduced risk of total preeclampsia in all participants, participants who smoked during pregnancy, participants who didn’t smoke during pregnancy, and participants with T1 or T2 DM (but not GDM). Stronger associations were generally observed among nulliparous participants and participants with pre-pregnancy BMI <30 kg/m^2^, whereas weaker or statistically non-significant associations were observed among multiparous participants and participants with pre-pregnancy BMI ≥30 kg/m^2^. An article from the China-based Born in Shenyang Cohort Study (BISCS) cohort^12^ reported that greater alignment with the ‘Sweet food-seafood TFD’ DP and the ‘Fish-seafood-FFQ’ DP was associated with lower risk of gestational hypertension among those with pre-pregnancy BMI ≥24 kg/m^2^, but not among those with pre-pregnancy BMI <24 kg/m^2^. A third article from the Danish National Birth Cohort^13^ noted that greater alignment with the ‘Seafood’ DP was associated with lower risk of gestational hypertension in all participants, participants with pre-pregnancy BMI 18.5-24.9 kg/m^2^, and participants with both male and female (trend neared significance) fetuses, but not in participants with pre-pregnancy BMI <18.5 kg/m^2^ or ≥25 kg/m^2^. Greater alignment with the ‘Seafood’ DP was associated with lower risk of preeclampsia in all participants, but the association was not statistically significant in any subgroup analysis.

Two articles from the Generation R Study^20,^ ^22^ found that lower alignment with a DP was associated with greater risk of HDP and/or blood pressure compared to high alignment.^20,^ ^22^ Lower alignment with DASH^22^ or the ‘Mediterranean’ DP^20^ was associated with higher diastolic blood pressure during middle and/or late pregnancy. Lower alignment with the ‘Mediterranean’ DP, but not DASH, was associated with higher systolic blood pressure in mid pregnancy and a higher risk of both gestational hypertension and preeclampsia.

Li et al. analyzed results from the NICHD Fetal Growth Studies–Singletons cohort^14^ and found that greater alignment with DASH, alternate Mediterranean Diet, and Alternative Healthy Eating Index were associated with reduced risk of gestational hypertension and/or preeclampsia, but the results varied by timing of dietary assessment (8-13 GW, 16-22 GW, and 24-29 GW) and by which quartiles were compared.

An article from an Iran-based cohort study^9^ reported that greater alignment with the ‘Healthy’ DP was marginally associated with reduced risk of preeclampsia but not risk of high diastolic or systolic blood pressure. Hajianfar et al. also reported that alignment with the highest quartile of the ‘Western’ DP was associated with reduced risk of high diastolic blood pressure when compared to the lowest quartile, but the overall association across quartiles was not statistically significant. In addition, greater alignment with the ‘Western’ DP was associated with reduced risk of high systolic blood pressure across quartiles. This contrasts with results from the same study, in which the ‘Western’ DP is associated with higher risk of preeclampsia, which is detailed below.

Seven articles reported statistically non-significant results that tended to be in the same direction as statistically significant results.^8,^ ^9,^ ^12,^ ^18,^ ^19,^ ^22,^ ^23^ Three articles reported statistically non-significant results that tended to be in the opposite direction as statistically significant results, meaning that dietary patterns commonly considered “detrimental” suggested a beneficial association with risk of HDP and/or blood pressure.^2,^ ^4,^ ^13^

#### Studies that suggest an association between dietary patterns and higher risk of HDP

No dietary patterns based on indices/scores were statistically significantly associated with a higher risk of HDP and/or higher blood pressure. The following dietary patterns derived via factor or cluster analysis were statistically significantly associated with higher risk of HDP and/or higher blood pressure: ‘Western’ DP,^9,^ ^13^ ‘Processed’ DP,^2^ ‘Traditional’ DP,^20^ and a ‘Rice/Pasta/Poultry’ DP.^13^ The following dietary patterns derived via factor or cluster analysis suggested a detrimental association with risk of HDP and/or blood pressure, despite a lack of statistically significant results: ‘Fish, poultry, and vegetables-based’ DP,^4^ ‘Snacks’ DP,^8^ ‘Vegetable/Prudent’ DP,^13^ ‘Sweets’ DP,^13^ ‘Obesogenic’ DP vs. ‘Traditional’ DP,^17^ and ‘Intermediate’ vs. ‘Traditional’ DP.^17^ These patterns were generally characterized by higher intakes of vegetables (primarily potatoes and French Fries), refined grains, and added sugars. There were few other consistencies among the dietary patterns.

Results and methods of interest from these articles are included below and in Table 7.

The Iran-based cohort study^9^ previously mentioned above also reported that greater alignment with the ‘Western’ DP was associated with higher risk of preeclampsia. This contrasts with results from the same study that the ‘Western’ DP is associated with lower risk of high diastolic and systolic blood pressure.

An article from the Danish National Birth Cohort^13^ also found that greater alignment with the ‘Western’ DP was associated with higher risk of preeclampsia and gestational hypertension, although results varied by pre-pregnancy BMI, fetal sex, and timing and severity of the diagnosis. Ikem et al. additionally reported that greater alignment with the ‘Rice/Pasta/Poultry’ DP was associated with higher risk of gestational hypertension, but not risk of preeclampsia or severe preeclampsia.

Timmermans et al. noted in their analysis of the Generation R Study^20^ that greater alignment with the ‘Traditional’ DP was associated with higher risk of both gestational hypertension and preeclampsia, as well as higher systolic blood pressure in both mid and later pregnancy, but results for diastolic blood pressure were inconsistent.

Three articles reported statistically non-significant results that tended to be in the same direction as statistically significant results.^8,^ ^13,^ ^17^ Two articles reported statistically non-significant results that tended to be in the opposite direction as statistically significant results, meaning that dietary patterns commonly considered

“beneficial” suggested a detrimental association with risk of HDP and/or blood pressure.^4,^ ^13^

#### Studies that report unclear statistically non-significant findings

Half of observational study articles reported statistically non-significant results that indicated a null association^2,^ ^3,^ ^7,^ ^13^ or that were unclear^1,^ ^8,^ ^9,^ ^12–14,^ ^17^ due to due to analyses which compared one dietary pattern to a different dietary pattern,^17^ dietary patterns with combinations of foods that were difficult to interpret,^8,^ ^9,^ ^12,^ ^13^ and/or reported results by quantiles did not show a suggested trend in direction.^1,^ ^8,^ ^9,^ ^12,^ ^14^

## Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee did not draw a conclusion statement for the systematic review question, “What is the relationship between dietary patterns consumed during pregnancy and risk of hypertensive disorders of pregnancy?” based on their review of the body of evidence. (see Table 6)

A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of hypertensive disorders of pregnancy because of substantial concerns with consistency, directness, and precision in the body of evidence. (Grade: Grade Not Assignable)

Table 6 Conclusion statement, grade for dietary patterns consumed during pregnancy and risk of hypertensive disorders of pregnancy

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of hypertensive disorders of pregnancy because of substantial concerns with consistency, directness, and precision in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 31 articles: 16 prospective cohort studies, 6 randomized controlled trials, 1 non-randomized controlled trial
Rationale | None of the intervention studies were designed to directly examine the relationship between dietary patterns during pregnancy and risk of hypertensive disorders during pregnancy, and the low incidence of the outcome limited precision of results. In addition, the available evidence was too inconsistent, both in the composition of the dietary patterns and the direction of the results, to draw a conclusion.

None of the intervention studies were designed to directly examine the relationship between dietary patterns during pregnancy and hypertensive disorders of pregnancy. Accordingly, the intervention studies were not sufficiently powered to detect differences between groups in the relatively rare outcome. In observational study articles, power analyses were not commonly reported and there was only one that noted having a large enough sample size to detect differences in an HDP outcome with adequate statistical power. Additionally, there were substantial inconsistencies in the direction of results from both the intervention study and observational study articles. Some dietary patterns with similar foods and beverages had a beneficial, detrimental, and/or non-significant association with the outcomes. Therefore, it was not possible to identify a combination of foods and beverages that were consistently associated with risk of HDP and/or blood pressure.

In addition, only 2 cohorts (MoBa and the Danish National Birth Cohort) noted large enough sample sizes to estimate risk of hypertensive disorders of pregnancy with significant statistical power.

More than half of the trials had high risk of bias overall due to concerns about deviations from intended interventions and selective reporting of the results. For deviations from intended interventions, issues arose when more participants in one group were diagnosed with GDM and the trial reported risk of HDP, which likely occurs after a GDM diagnosis. If participants diagnosed with GDM were treated with diet or insulin and GDM rates differed between the intervention and control group, this could have affected the HDP results later in pregnancy. There were also concerns about selective reporting of results when there was no pre-specified analysis plan, when there were more analyses listed in the protocol than what was reported in the article, or when there was not strong justification for secondary analyses in a subset of participants that were not specified in the original protocol. Risk of bias domain ratings for intervention study articles can be found in Table 8 and Table 9.

All observational study articles had overall high risk of bias due to concerns about confounding, post-exposure interventions, missing data, and selective reporting of the results. Only a handful of observational studies controlled for all key confounders while also not controlling for any post-exposure variables (e.g., gestational weight gain). Issues arose for post-exposure interventions when GDM rates differed by alignment to a dietary pattern(s), but GDM was not controlled for in the analyses. Selection bias was suspected if participants were excluded from the study or analysis based on characteristics that were observed after the start of the exposure that were likely to have been influenced by both the exposure and the outcome. Some articles also did not report adequate information on missing data or did not perform analyses to suggest the results were not biased by missing data. Concerns about selection of the reported result were due to the lack of a pre-specified analysis plan or suspicion that results may have been selected based on magnitude or statistical significance. Risk of bias domain ratings for observational study articles can be found in Table 10.

Publication bias is always a concern and is a risk in this systematic review because the search did not include the gray literature. However, this body of evidence includes articles with both large and small sample sizes, as well as significant and null findings, so publication bias may be less likely.