# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by a data visualization table (Table A 14) that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence. During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components in the dietary patterns studied along with the direction, magnitude, and statistical significance of reported results. Detailed information about the body of evidence, including a description of each dietary pattern in more detail, study and population characteristics, outcomes, key confounders accounted for, and funding sources, are summarized in the evidence tables of this report (Table 5 and Table 7).

Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. Two additional columns, “Other, A” and “Other, B” , captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast food, ready-to-eat dishes, pizza, and chocolate. Multiple symbols in each cell mean that the dietary pattern included multiple components from that column/category. Empty cells mean that the dietary pattern did not include a component within that column/category.

Table A 14 Visualization of dietary pattern components organized by approach across evidence examining the relationship between dietary patterns consumed during pregnancy and hypertensive disorders of pregnancy^*^,^†^

Article; Dietary pattern | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish, Seafood | Meats (Red Processed) | Lean meats (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | SSB | Sugary Foods | Fat: Unsaturated, Oils | Fat: Other | Fat: Saturated | Alcohol | Sodium | Tea and Coffee | Other A | Other B
RCT
Al Wattar, 2019;^24^ Mediterranean (Med.) w/ mixed nuts + EVOO | ▲ | | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼
Assaf-Balut, 2017;^25^ Med. w/ mixed nuts + EVOO | ▲ | | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | ▲ | | | ▲
Assaf-Balut, 2019;^26^ Med. w/ mixed nuts + EVOO | ▲ | | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | ▲ | | | ▲
Melero, 2020;^30^ Med. w/ mixed nuts + EVOO | ▲ | | ▲ | | | ▲ N | | | | ▲ F | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | | | | ▲
Zhao, 2022;^31^ Med. w/ recommended pistachios + EVOO | ▲ | | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | ▲ R W | | | ▲
Dodd, 2019;^28^ Australian dietary standards | ▲ | | | ▲ | | | | | | | | | | ▲
Crovetto, 2021;^27^ Med. w/ walnuts + EVOO | ▲ | | ▲ | ▲ | | ▲ N | ▲ | | ▼ | ▲ F | ▼ RP | ▲ | | ▲ | | | ▼ | ▼ | ▲ OO | | ▼ | | | | ▲
Khoury, 2005;^29^ Cholesterol-lowering diet | ▲ | | | ▲ | | ▲ | | | | | ▼ M | M | | | | ▼ | | | ▲ OO | | ▼
NRCT
Melero, 2020;^30^ Med. w/ mixed nuts + EVOO | ▲ | | ▲ | | | ▲ N | | | | ▲ F | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | | | | ▲
Index/Score
Arvizu, 2020;^1^ DASH | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Fulay, 2018;^7^ DASH | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Fulay, 2018;^7^ DASH OMNI | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | ▲ MUFA +PUFA | | | | ▼
Li, 2021;^14^ DASH | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Wiertsema, 2021;^22^ DASH | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Courtney, 2020;^3^ Modified DASH | ▲ | | ▲ LNS | ▲ | Fr | LNS | ▲ | | | | ▼ RP | | | | ▲ | | ▼ SW | SW | | | | | ▼
Miller, 2022;^18^ Modified DASH | ▲ | | ▲ LNS | ▲ | ▼ JSS B | LNS | ▲ | | | ▲ F | ▼ RP | | | | ▲ | | JSS B | | | | | | ▼
Makarem, 2022;^16^ aMED | ▲ | | ▲ | ▲ | | ▲ N | ▲ | | | ▲ F | ▼ RP | | | | | | | | ▲ MUFA:SF A | | MUFA:SF A | ◄
Miller, 2022;^18^ aMED | ▲ | | ▲ | ▲ | | ▲ N | ▲ | | | ▲ F | ▼ RP | | | | | | | | ▲ MUFA:SF A | | MUFA:SF A | ◄
Li, 2021;^14^ aMED | ▲ | | | ▲ | | ▲ N | | ◄ | | ▲ F | ▼ RP | ▲ | | ◄ | | | | | | | | | ▼
Flor-Alemany, 2021;^6^ MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ F | ▼ RP | ▼ | | | | ▼ | | | ▲ OO
Li, 2021;^14^ AHEI-2010 | ▲ | | ▲ LN | ▲ | ▼ | LN | ▲ | | | | ▼ RP | | | | | | ▼ | | ▲ n-3; PUFA
Yee, 2020;^23^ HEI-2010 | ▲ | | ▲ PR O | ▲ | Fr | PR O | ▲ | | ▼ | PR O | PR O | PR O | PR O | ▲ | | | ▼ AS | AS | ▲ | | ▼ | ▼ | ▼
Miller, 2022;^18^ HEI-2015 | ▲ | | ▲ PR O | ▲ | Fr | PR O | ▲ | | ▼ | PR O | PR O | PR O | PR O | ▲ | | | ▼ AS | AS | ▲ PUFA+ MUFA: SFA | | ▼ | ▼ | ▼
Arvizu, 2020;^1^ AHA Primary | ▲ | | | ▲ | | | ▲ | | | ▲ | | | | | | | ▼ | | | | | | ▼
Arvizu, 2020;^1^ AHA Secondary | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | ▼ P | | | | | | ▼ | | | | | | ▼
Rifas-Shiman, 2009;^19^ Alternate HEI-P | ▲ | | | ▲ | | | | | | ▲ W:R | W:R | W:R | | | | | | | ▲ PUFA: SFA | ▼ TFA | PUFA: SFA | | | | ▲
Ding, 2021;^5^ CDGCI-PW | ▲ | ▲ | ▲ | | | ▲ N | | ▲ | | ▲ S | ▲R | ▲ | | ▲ | | | | ▼ | | | | | ▲ | | | ▼
Hillesund, 2014;^10^ NND | ▲ | | | ▲ | ▼ MI:J | | ▲ WG : RG | | WG : RG | ▲ | ▲ M | M | | MI: J | | | | ▼ W: SS B | | | | | | | ▲ | W: SS B
Hillesund, 2018;^11^ NFFD Diet | ▲ | | | ▲ | | | | | | | | | | | | | ▼ AS | AS | | | | | ▼ | | ▲ | ▼
Factor/Cluster
Brantsæter, 2009;^2^ Vegetable | ▲ | | | ▲ | | | | ▲ | | | | ▲ | | | | | | | ▲
Brantsæter, 2009;^2^ Processed food | | ▲ F F | | | | | ▼ | | ▲ | ▼ F | ▲ P | | | | | | ▲ | | | | | | | | ▲
Brantsæter, 2009;^2^ Potato and fish | | ▲ | | | | | | | | ▲ | ▲ M | M | | | | | | | ▲
Brantsæter, 2009;^2^ Cakes and sweets | | | | | | | | ▲ | | | | | | | | | | ▲
de Seymour, 2022;^4^ Fish, poultry and vegetables-based | ▲ | | ▲ | ▲ | | ▲ N | | ▲ | | ▲ | ▲ R | ▲ | ▲ | ▲ | | | | | | | | | | | ▲
de Seymour, 2022;^4^ Pasta, sweetened beverages, oils and condiments-based | | | | | | | | ▲ | | | | | | | | | ▲ | | ▲ OC | | OC | | | | ▲
Flynn, 2016;^8^ Fruit & Veg | ▲ | | ▲ | ▲ | | | | | | | | | | ▲ Y
Flynn, 2016;^8^ African/Caribbea n | | ▲ | | ▲ | | | | ▲ | | ▲ F | ▲ RW | RW
Flynn, 2016;^8^ Processed | ▲ | ▲ | | | | | | | | | ▲ P | | | | | | ▲ | ▲ | | | | | | | ▲
Flynn, 2016;^8^ Snacks | | | | | | | | | | | | | | ▲ CH | | | | ▲
Hajianfar, 2018;^9^ Healthy | ▲ | | | ▲ | | ▲ N | | | | ▲ F | ▲ R | ▲ | ▲ | | ▲ | | | | ▲ | | | | | | ▲
Hajianfar, 2018;^9^ Western | | ▲ | ▲ | ▲ | ▲ | ▲ N | ▲ | | | ▲ F | ▲ P | | ▲ | | | ▲ | ▲ ▲ AS | ▲ AS | | | ▲ | | | ▲ C | ▲
Hajianfar, 2018;^9^ Traditional | ▲ | | | | | | | | ▲ | | | | | | | | ▲ AS | AS | ▲ | | | | ▲ | ▲ T | ▲
Hu, 2022;^12^ Traditional-TFD | ▲ | ▲ | | ▲ | | ▲ N | ▲ | ▲ | | | ▲ R
Hu, 2022;^12^ Wheaten food-coarse cereals-TFD | | | ▲ | | | | ▲ | | ▼ | | | | ▼
Hu, 2022;^12^ Sweet food-seafood-TFD | | | | ▲ | | | | | | ▲ S | | | | | | | ▲ | ▲
Hu, 2022;^12^ Fried food-protein-rich-TFD | | | ▲ | | | | | | | | | | | ▲ | | | | | | | | | | | ▲
Hu, 2022;^12^ Fish-seafood-FFQ | ▲ | | | | | | | | | ▲ | ▲ R | ▲
Hu, 2022;^12^ Protein-rich FFQ | | | ▲ | | | ▲ N | | | | | | | ▲ | ▲ | | | | ▲
Hu, 2022;^12^ Vegetable-fruit-rice-FFQ | ▲ | | | ▲ | | ▲ N | | ▲
Ikem, 2019;^13^ Western | | ▲ ▲ F F | | | | | | | ▲ | ▲ F | ▲ M | M | ▲ | | | | | | ▲ | | ▲ | | | | ▲
Ikem, 2019;^13^ Vegetable/ Prudent | ▲ | | ▲ | ▲
Ikem, 2019;^13^ Seafood | ▲ | | | | | | | | | ▲ | ▲ R | | ▲ | ▲ | | | | | ▲
Ikem, 2019;^13^ Nordic | | | | ▲ | | | ▲ | | | | ▲ M | M | | | | ▲ | | ▲
Ikem, 2019;^13^ Rice/Pasta/Poultr y | | | | | | | | ▲ | | | | ▲
Ikem, 2019;^13^ Sweets | | ▲ F F | | | | | | | ▲ | | | | | | | | | ▲ | ▲ | | | | | | ▲
Ikem, 2019;^13^ Alcohol | ▲ | | ▲ | ▲ | | | | | | | | | | | | | | | | | | ▲
Jarman, 2018;^15^ Healthy | ▲ | | | ▲ | | | ▲ | | ▲ | ▲ | | | | | | | | | ▲
Miele, 2021;^17^ Obesogenic | | | | | | | | | ▲ | | | | | | | | | ▲ | ▲ Fats | Fat s | Fats | | | | ▲ U P
Miele, 2021;^17^ Intermediate | | | | | | | | | ▼ | | | | | | | | | ▼ | ▼ Fats | Fat s | Fats | | | | | ▼ UP
Miele, 2021;^17^ Vegetarian | ▲ | | | ▲ | | | | | | | | | | ▲
Miele, 2021;^17^ Protein | | | ▲ | | | | | | | | ▲ | | ▲ | | | | | | | | | | | | | ▼
Miele, 2021;^17^ Traditional | | | ▲ | | | | | | | | ▲ M | M | ▲ | | | | | | | | | | | | ▲
Timmermans, 2011;^20^ Mediterranean | ▲ | | ▲ | | | | | ▲ | | ▲ F | | | | | | | | ▼ | ▲ | | | ◄
Timmermans, 2011;^20^ Traditional | | ▲ | | ▼ | | | | ▼ | | ▼ F | ▲ M | M | | | | | | | | | | | | | | ▼
Torjusen, 2014;^21^ Health and sustainability | ▲ | ▼ F F | | ▲ | | | ▲ | | ▼ | | ▼ M | M | | | | | | ▼ | ▲ | | | | ▼

* ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern.

† Abbreviations: AS, added sugar; C, coffee; CH, cheese; F, fish; FF, fried potato; Fr, included with Fruit component; JSSB, fruit juice and SSB; LN, legumes and nuts; LNS, legumes, nuts, and seeds; MI:J, ratio of milk to juice; MUFA, monounsaturated fatty acids; M, meat and/or meat products; N, nuts; n-3, omega-3 fatty acids; OC, oils and condiments; OO, olive oil; PRO, protein; PUFA, polyunsaturated fatty acids; RP, red and processed meat; RW, red and white meat; S, seafood; SFA, saturated fatty acids; SW, sweet snacks, SSB, and desserts; T, tea; TFA, trans fatty acids; UP, ultra-processed foods; W:R, ratio of white to red meat; W:SSB, ratio of water to SSB, WG:RG, ratio of whole grain bread to refined grain bread; Y, yogurt