# Appendix 5 Excluded articles

The existing systematic review^*^ for this question included 8 articles. However, after applying the inclusion and exclusion criteria established for the update to that review, only 6 remained eligible for inclusion. The following articles were excluded from the existing systematic review due to updated life stage eligibility criteria:

1. Schoenaker DA, Soedamah-Muthu SS, Mishra GD. Quantifying the mediating effect of body mass index on the relation between a Mediterranean diet and development of maternal pregnancy complications: the Australian Longitudinal Study on Women’s Health. Am J Clin Nutr 2016;104(3):638-45.
2. Schoenaker DA, Soedamah-Muthu SS, Callaway LK, Mishra GD. Prepregnancy dietary patterns and risk of developing hypertensive disorders of pregnancy: results from the Australian Longitudinal Study on Women’s Health. Am J Clin Nutr 2015;102(1):94-101.

* Raghavan R, Dreibelbis C, Kingshipp BJ, . Dietary Patterns before and during Pregnancy and Risk of Hypertensive Disorders of Pregnancy: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0101

The following tables list the articles excluded after full-text screening for the updated systematic review literature search (Appendix 4). Articles excluded from Search A are in Table A 2 and articles excluded from Search B are in Table A 3. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 12 Search A articles excluded after full text screening

| Citation | Rationale
1 | Alamolhoda, SH, Simbar, M, Mirmiran, P, Mirabi, P. The effectiveness of low trans-fatty acids dietary pattern in pregnancy and the risk of gestational diabetes mellitus. Caspian J Intern Med. 2019. 10:197–204. doi:10.22088/cjim.10.2.197 | Intervention/Exposure
2 | Allman, BrittanyR, Diaz Fuentes, Eva, Williams, Keith D, Turner, DonaldE, Andres, Aline, Børsheim, Elisabet. Obesity Status Affects the Relationship Between Protein Intake and Insulin Sensitivity in Late Pregnancy. Nutrients. 2019. 11:2190. doi:10.3390/nu11092190 | Intervention/Exposure
3 | Anand, SS, Gupta, M, Teo, KK, Schulze, KM, Desai, D, Abdalla, N, Zulyniak, M, de Souza, R, Wahi, G, Shaikh, M, Beyene, J, de Villa, E, Morrison, K, McDonald, SD, Gerstein, H. Causes and consequences of gestational diabetes in South Asians living in Canada: results from a prospective cohort study. CMAJ Open. 2017. 5:E604-e611. doi:10.9778/cmajo.20170027 | Study Design
4 | Arredondo, Armando, Torres, Christian, Orozco, Emanuel, Pacheco, Selene, Huang, Fengyang, Zambrano, Elena, Bolaños-Jiménez, Francisco, Bolaños-Jiménez, Francisco. Socio-economic indicators, dietary patterns, and physical activity as determinants of maternal obesity in middle-income countries: Evidences from a cohort study in Mexico. International Journal of Health Planning & Management. 2019. 34:e713-e725. doi:10.1002/hpm.2684 | Outcome; Comparator
5 | Arvizu, M, Afeiche, MC, Hansen, S, Halldorsson, TF, Olsen, SF, Chavarro, JE. Fat intake during pregnancy and risk of preeclampsia: a prospective cohort study in Denmark. Eur J Clin Nutr. 2019. 73:1040–1048. doi:10.1038/s41430-018-0290-z | Intervention/Exposure
6 | Assaf-Balut, C, Garcia de la Torre, N, Durán, A, Bordiu, E, Del Valle, L, Familiar, C, Valerio, J, Jimenez, I, Herraiz, MA, Izquierdo, N, Runkle, I, de Miguel, MP, Montañez, C, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. An Early, Universal Mediterranean Diet-Based Intervention in Pregnancy Reduces Cardiovascular Risk Factors in the “Fourth Trimester”. J Clin Med. 2019. 8. doi:10.3390/jcm8091499 | Study Design
7 | Barabash, ANA, Valerio Deogracia, Johanna, Assaf-Balut, Carla, Del Valle, Laura, De La Torre, Nuria Garcia, Bordiu, Elena, Duran, Alejandra, Fuentes, Manuel, Ines Sr, Jimenez, Cuesta, Martin, Rubio, MiguelA, Calle, AlfonsoL. 193-LB: Levels of Adherence to a Mediterranean Diet and Risk of Gestational Diabetes Mellitus: Modulation Effects of MTNRB1_rs10830963, TCFTL2_rs7903146, and MC4R_rs17782313 Gene Polymorphisms. Diabetes. 2019. 68. doi:10.2337/db19-193-LB | Publication Status
8 | Bartáková, V, Kuricová, K, Zlámal, F, Bělobrádková, J, Kaňková, K. Differences in food intake and genetic variability in taste receptors between Czech pregnant women with and without gestational diabetes mellitus. Eur J Nutr. 2018. 57:513–521. doi:10.1007/s00394-016-1334-6 | Study Design
9 | Broekhuizen, K, Simmons, D, Devlieger, R, van Assche, A, Jans, G, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Desoye, G, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LL, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Snoek, FJ, Jelsma, JGM, Bosmans, JE, van Poppel, MNM, van Dongen, JM. Cost-effectiveness of healthy eating and/or physical activity promotion in pregnant women at increased risk of gestational diabetes mellitus: economic evaluation alongside the DALI study, a European multicenter randomized controlled trial. Int J Behav Nutr Phys Act. 2018. 15:23. doi:10.1186/s12966-018-0643-y | Intervention/Exposure
10 | Bruno, R, Petrella, E, Bertarini, V, Pedrielli, G, Neri, I, Facchinetti, F. Adherence to a lifestyle programme in overweight/obese pregnant women and effect on gestational diabetes mellitus: a randomized controlled trial. Matern Child Nutr. 2017. 13. doi:10.1111/mcn.12333 | Intervention/Exposure
11 | Carlos, S, De La Fuente-Arrillaga, C, Bes-Rastrollo, M, Razquin, C, Rico-Campà, A, Martínez-González, MA, Ruiz-Canela, M. Mediterranean diet and health outcomes in the SUN cohort. Nutrients. 2018. 10. doi:10.3390/nu10040439 | Study Design; Data Overlap
12 | Carolan-Olah, M, Sayakhot, P. A randomized controlled trial of a web-based education intervention for women with gestational diabetes mellitus. Midwifery. 2019. 68:39–47. doi:10.1016/j.midw.2018.08.019 | Health Status; Life Stage
13 | Chen, Q, Feng, Y, Yang, H, Wu, W, Zhang, P, Wang, K, Wang, Y, Ko, J, Shen, J, Guo, L, Zhao, F, Du, W, Ru, S, Wang, S, Zhang, Y. A Vitamin Pattern Diet Is Associated with Decreased Risk of Gestational Diabetes Mellitus in Chinese Women: Results from a Case Control Study in Taiyuan, China. J Diabetes Res. 2019. 2019:5232308. doi:10.1155/2019/5232308 | Study Design
14 | Chen, X, de Seymour, JV, Han, TL, Xia, Y, Chen, C, Zhang, T, Zhang, H, Baker, PN. Metabolomic biomarkers and novel dietary factors associated with gestational diabetes in China. Metabolomics. 2018. 14:149. doi:10.1007/s11306-018-1445-6 | Study Design
15 | Compher, Charlene, Elovitz, MichalA, Parry, SamuelI, Chittams, Jesse, Griffith, CodyJ. 330: Diet pattern is associated with an increased risk of hypertensive disorders of pregnancy. American Journal of Obstetrics & Gynecology. 2018. 218:S206-S206. doi:10.1016/j.ajog.2017.10.266 | Publication Status
16 | de la Torre, NG, Assaf-Balut, C, Jiménez Varas, I, Del Valle, L, Durán, A, Fuentes, M, Del Prado, N, Bordiú, E, Valerio, JJ, Herraiz, MA, Izquierdo, N, Torrejón, MJ, Cuadrado, MA, de Miguel, P, Familiar, C, Runkle, I, Barabash, A, Rubio, MA, Calle-Pascual, AL. Effectiveness of Following Mediterranean Diet Recommendations in the Real World in the Incidence of Gestational Diabetes Mellitus (GDM) and Adverse Maternal-Foetal Outcomes: A Prospective, Universal, Interventional Study with a Single Group. The St Carlos Study. Nutrients. 2019. 11. doi:10.3390/nu11061210 | Comparator
17 | Deniz, ÇD, Özler, S, Sayın, FK, Eryılmaz, MA. Associations between night eating syndrome and metabolic parameters in pregnant women. Turkish Journal of Obstetrics and Gynecology. 2019. 16:107–111. doi:10.4274/tjod.galenos.2019.77864 | Intervention/Exposure
18 | Donazar-Ezcurra, M, Lopez-Del Burgo, C, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, de Irala, J, Bes-Rastrollo, M. Pre-pregnancy adherences to empirically derived dietary patterns and gestational diabetes risk in a Mediterranean cohort: the Seguimiento Universidad de Navarra (SUN) project. Br J Nutr. 2017. 118:715–721. doi:10.1017/s0007114517002537 | Life Stage
19 | Donazar-Ezcurra, M, Lopez-Del Burgo, C, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, de Irala, J, Bes-Rastrollo, M. Soft drink consumption and gestational diabetes risk in the SUN project. Clin Nutr. 2018. 37:638–645. doi:10.1016/j.clnu.2017.02.005 | Intervention/Exposure
20 | Dong, JY, Kimura, T, Ikehara, S, Cui, M, Kawanishi, Y, Yamagishi, K, Ueda, K, Iso, H. Chocolate consumption and risk of gestational diabetes mellitus: The Japan Environment and Children’s Study. British Journal of Nutrition. 2019. 122:936–941. doi:10.1017/S0007114519001806 | Intervention/Exposure
21 | Duran, Alejandra, De La Torre, Nuria Garcia, Assaf-Balut, Carla, Del Valle, Laura, Ines, Jimenez, Valerio Deogracia, Johanna, Bordiu, Elena, Fuentes, Manuel, Barabash, ANA, Cuesta, Martin, Rubio, MiguelA, Calle, AlfonsoL. 194-LB: Effectiveness of Following Mediterranean Diet (MedDiet) Recommendations in the Real World in the Incidence of Gestational Diabetes Mellitus (GDM) and Adverse Maternal-Fetal Outcomes: A Prospective, Universal Interventional Study. Diabetes. 2019. 68. doi:10.2337/db19-194-LB | Publication Status
22 | Elvebakk, T, Mostad, IL, Mørkved, S, Salvesen, K. Dietary Intakes and Dietary Quality during Pregnancy in Women with and without Gestational Diabetes Mellitus-A Norwegian Longitudinal Study. Nutrients. 2018. 10. doi:10.3390/nu10111811 | Intervention/Exposure
23 | Emond, JA, Karagas, MR, Baker, ER, Gilbert-Diamond, D. Better Diet Quality during Pregnancy Is Associated with a Reduced Likelihood of an Infant Born Small for Gestational Age: An Analysis of the Prospective New Hampshire Birth Cohort Study. J Nutr. 2018. 148:22–30. doi:10.1093/jn/nxx005 | Confounders
24 | Englund-Ögge, L, Brantsæter, AL, Juodakis, J, Haugen, M, Meltzer, HM, Jacobsson, B, Sengpiel, V. Associations between maternal dietary patterns and infant birth weight, small and large for gestational age in the Norwegian Mother and Child Cohort Study. Eur J Clin Nutr. 2019. 73:1270–1282. doi:10.1038/s41430-018-0356-y | Outcome
25 | Epel, E, Laraia, B, Coleman-Phox, K, Leung, C, Vieten, C, Mellin, L, Kristeller, JL, Thomas, M, Stotland, N, Bush, N, Lustig, RH, Dallman, M, Hecht, FM, Adler, N. Effects of a Mindfulness-Based Intervention on Distress, Weight Gain, and Glucose Control for Pregnant Low-Income Women: A Quasi-Experimental Trial Using the ORBIT Model. Int J Behav Med. 2019. 26:461–473. doi:10.1007/s12529-019-09779-2 | Intervention/Exposure
26 | Fernández-Barrés, S, Vrijheid, M, Manzano-Salgado, CB, Valvi, D, Martínez, D, Iñiguez, C, Jimenez-Zabala, A, Riaño-Galán, I, Navarrete-Muñoz, EM, Santa-Marina, L, Tardón, A, Vioque, J, Arija, V, Sunyer, J, Romaguera, D. The Association of Mediterranean Diet during Pregnancy with Longitudinal Body Mass Index Trajectories and Cardiometabolic Risk in Early Childhood. J Pediatr. 2019. 206:119–127.e6. doi:10.1016/j.jpeds.2018.10.005 | Study Design
27 | Gadgil, MD, Ehrlich, SF, Zhu, Y, Brown, SD, Hedderson, MM, Crites, Y, Ferrara, A. Dietary Quality and Glycemic Control Among Women with Gestational Diabetes Mellitus. J Womens Health (Larchmt). 2019. 28:178–184. doi:10.1089/jwh.2017.6788 | Health Status
28 | Gicevic, S, Gaskins, AJ, Fung, TT, Rosner, B, Tobias, DK, Isanaka, S, Willett, WC. Evaluating pre-pregnancy dietary diversity vs. dietary quality scores as predictors of gestational diabetes and hypertensive disorders of pregnancy. PLoS One. 2018. 13:e0195103. doi:10.1371/journal.pone.0195103 | Life Stage
29 | Gnanendran, Subashini, Porrett, Jemma, Woods, Cindy, Buttrose, Maryke, Jukka, Clare, Hollins, Jane, Robson, Stephen, de Costa, Caroline. A randomised controlled trial of consumption of dark chocolate in pregnancy to reduce pre-eclampsia: Difficulties in recruitment, allocation and adherence. Australian & New Zealand Journal of Obstetrics & Gynaecology. 2018. 58:358–361. doi:10.1111/ajo.12694 | Intervention/Exposure; Publication Status
30 | Gonzalez-Nahm, S, Hoyo, C, Østbye, T, Neelon, B, Allen, C, Benjamin-Neelon, SE. Associations of maternal diet with infant adiposity at birth, 6 months and 12 months. BMJ Open. 2019. 9:e030186. doi:10.1136/bmjopen-2019-030186 | Outcome
31 | Goodarzi-Khoigani, M, Mazloomy Mahmoodabad, SS, Baghiani Moghadam, MH, Nadjarzadeh, A, Mardanian, F, Fallahzadeh, H, Dadkhah-Tirani, A. Prevention of Insulin Resistance by Dietary Intervention among Pregnant Mothers: A Randomized Controlled Trial. Int J Prev Med. 2017. 8:85. doi:10.4103/ijpvm.IJPVM_405_16 | Intervention/Exposure
32 | Goshtasebi, A, Hosseinpour-Niazi, S, Mirmiran, P, Lamyian, M, Moghaddam Banaem, L, Azizi, F. Pre-pregnancy consumption of starchy vegetables and legumes and risk of gestational diabetes mellitus among Tehranian women. Diabetes Res Clin Pract. 2018. 139:131–138. doi:10.1016/j.diabres.2018.02.033 | Intervention/Exposure
33 | Hamad, Rita, Collin, DanielF, Baer, RebeccaJ, Jelliffe-Pawlowski, LauraL. Association of Revised WIC Food Package With Perinatal and Birth Outcomes: A Quasi-Experimental Study. JAMA Pediatrics. 2019. 173:845–852. doi:10.1001/jamapediatrics.2019.1706 | Intervention/Exposure
34 | Harreiter, J, Simmons, D, Desoye, G, Corcoy, R, Adelantado, JM, Devlieger, R, Galjaard, S, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LLT, Dunne, F, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Mantaj, U, Hill, D, Jelsma, JGM, Snoek, FJ, Leutner, M, Lackinger, C, Worda, C, Bancher-Todesca, D, Scharnagl, H, van Poppel, MNM, Kautzky-Willer, A. Nutritional Lifestyle Intervention in Obese Pregnant Women, Including Lower Carbohydrate Intake, Is Associated With Increased Maternal Free Fatty Acids, 3-β-Hydroxybutyrate, and Fasting Glucose Concentrations: A Secondary Factorial Analysis of the European Multicenter, Randomized Controlled DALI Lifestyle Intervention Trial. Diabetes Care. 2019. 42:1380–1389. doi:10.2337/dc19-0418 | Intervention/Exposure
35 | Hellmuth, C, Lindsay, KL, Uhl, O, Buss, C, Wadhwa, PD, Koletzko, B, Entringer, S. Association of maternal prepregnancy BMI with metabolomic profile across gestation. Int J Obes (Lond). 2017. 41:159–169. doi:10.1038/ijo.2016.153 | Outcome
36 | Hezaveh, ZS, Feizy, Z, Dehghani, F, Sarbakhsh, P, Moini, A, Vafa, M. The Association between Maternal Dietary Protein Intake and Risk of Gestational Diabetes Mellitus. Int J Prev Med. 2019. 10:197. doi:10.4103/ijpvm.IJPVM_86_19 | Study Design
37 | Huang, L, Shang, L, Yang, W, Li, D, Qi, C, Xin, J, Wang, S, Yang, L, Zeng, L, Chung, MC. High starchy food intake may increase the risk of adverse pregnancy outcomes: a nested case-control study in the Shaanxi province of Northwestern China. BMC Pregnancy Childbirth. 2019. 19:362. doi:10.1186/s12884-019-2524-z | Outcome
38 | Huang, WQ, Lu, Y, Xu, M, Huang, J, Su, YX, Zhang, CX. Excessive fruit consumption during the second trimester is associated with increased likelihood of gestational diabetes mellitus: a prospective study. Sci Rep. 2017. 7:43620. doi:10.1038/srep43620 | Intervention/Exposure
39 | Jiang, F, Li, Y, Xu, P, Li, J, Chen, X, Yu, H, Gao, B, Xu, B, Li, X, Chen, W. The efficacy of the Dietary Approaches to Stop Hypertension diet with respect to improving pregnancy outcomes in women with hypertensive disorders. J Hum Nutr Diet. 2019. 32:713–718. doi:10.1111/jhn.12654 | Intervention/Exposure; Health Status; Outcome; Comparator
40 | Kozlowska, A, Jagielska, AM, Okreglicka, KM, Dabrowski, F, Kanecki, K, Nitsch-Osuch, A, Wielgos, M, Bomba-Opon, D. Dietary macronutrients and fluid intakes in a sample of pregnant women with either gestational diabetes or type 1 diabetes mellitus, assessed in comparison with Polish nutritional guidelines. Ginekol Pol. 2018. 89:659–666. doi:10.5603/GP.a2018.0111 | Study Design; Health Status
41 | Kunath, J, Günther, J, Rauh, K, Hoffmann, J, Stecher, L, Rosenfeld, E, Kick, L, Ulm, K, Hauner, H. Effects of a lifestyle intervention during pregnancy to prevent excessive gestational weight gain in routine care - the cluster-randomised GeliS trial. BMC Med. 2019. 17:5. doi:10.1186/s12916-018-1235-z | Intervention/Exposure
42 | Lamyian, M, Hosseinpour-Niazi, S, Mirmiran, P, Moghaddam Banaem, L, Goshtasebi, A, Azizi, F. Pre-Pregnancy Fast Food Consumption Is Associated with Gestational Diabetes Mellitus among Tehranian Women. Nutrients. 2017. 9. doi:10.3390/nu9030216 | Intervention/Exposure
43 | Lavie, M, Lavie, I, Maslovitz, S. Paleolithic diet during pregnancy-A potential beneficial effect on metabolic indices and birth weight. Eur J Obstet Gynecol Reprod Biol. 2019. 242:7–11. doi:10.1016/j.ejogrb.2019.08.013 | Comparator; Data Overlap
44 | Liang, Y, Gong, Y, Zhang, X, Yang, D, Zhao, D, Quan, L, Zhou, R, Bao, W, Cheng, G. Dietary Protein Intake, Meat Consumption, and Dairy Consumption in the Year Preceding Pregnancy and During Pregnancy and Their Associations With the Risk of Gestational Diabetes Mellitus: A Prospective Cohort Study in Southwest China. Front Endocrinol (Lausanne). 2018. 9:596. doi:10.3389/fendo.2018.00596 | Intervention/Exposure
45 | Liang, Z, Wang, L, Liu, H, Chen, Y, Zhou, T, Heianza, Y, Leng, J, Li, W, Yang, X, Shen, Y, Gao, R, Hu, G, Qi, L. Genetic susceptibility, lifestyle intervention and glycemic changes among women with prior gestational diabetes. Clin Nutr. 2020. 39:2144–2150. doi:10.1016/j.clnu.2019.08.032 | Intervention/Exposure; Country; Life Stage
46 | Looman, M, Geelen, A, Samlal, RAK, Heijligenberg, R, Klein Gunnewiek, JMT, Balvers, MGJ, Wijnberger, LDE, Brouwer-Brolsma, EM, Feskens, EJM. Changes in Micronutrient Intake and Status, Diet Quality and Glucose Tolerance from Preconception to the Second Trimester of Pregnancy. Nutrients. 2019. 11. doi:10.3390/nu11020460 | Study Design; Life Stage
47 | Marí-Sanchis, Amelia, Díaz-Jurado, Ginette, Basterra-Gortari, Javier F, de la Fuente-Arrillaga, Carmen, Martínez-González, MiguelA, Bes-Rastrollo, Maira. Association between pre-pregnancy consumption of meat, iron intake, and the risk of gestational diabetes: the SUN project. European Journal of Nutrition. 2018. 57:939–949. doi:10.1007/s00394-017-1377-3 | Intervention/Exposure
48 | Maslova, Ekaterina, Hansen, Susanne, Strøm, Marin, Halldorsson, ThorhallurI, Grunnet, LouiseG, Vaag, AllanA, Olsen, SjurdurF. Fish Intake in Pregnancy and Offspring Metabolic Parameters at Age 9–16—Does Gestational Diabetes Modify the Risk?. Nutrients. 2018. 10:1534. doi:10.3390/nu10101534 | Intervention/Exposure
49 | Meinilä, J, Valkama, A, Koivusalo, SB, Rönö, K, Kautiainen, H, Lindström, J, Stach-Lempinen, B, Eriksson, JG, Erkkola, M. Association between diet quality measured by the Healthy Food Intake Index and later risk of gestational diabetes-a secondary analysis of the RADIEL trial. Eur J Clin Nutr. 2017. 71:913. doi:10.1038/ejcn.2017.66 | Publication Status
50 | Mendoza, LC, Harreiter, J, Simmons, D, Desoye, G, Adelantado, JM, Juarez, F, Chico, A, Devlieger, R, van Assche, A, Galjaard, S, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LLT, Tanvig, M, Lapolla, A, Dalfra, MG, Bertolotto, A, Mantaj, U, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Jelsma, JG, Snoek, FJ, van Poppel, MNM, Worda, C, Bancher-Todesca, D, Kautzky-Willer, A, Dunne, FP, Corcoy, R. Risk factors for hyperglycemia in pregnancy in the DALI study differ by period of pregnancy and OGTT time point. Eur J Endocrinol. 2018. 179:39–49. doi:10.1530/eje-18-0003 | Intervention/Exposure
51 | Mi, B, Wen, X, Li, S, Liu, D, Lei, F, Liu, R, Shen, Y, Chen, Y, Zeng, L, Liu, X, Dang, S, Yan, H. Vegetable dietary pattern associated with low risk of preeclampsia possibly through reducing proteinuria. Pregnancy Hypertens. 2019. 16:131–138. doi:10.1016/j.preghy.2019.04.001 | Study Design
52 | Mirmiran, P, Hosseinpour-Niazi, S, Moghaddam-Banaem, L, Lamyian, M, Goshtasebi, A, Azizi, F. Inverse relation between fruit and vegetable intake and the risk of gestational diabetes mellitus. Int J Vitam Nutr Res. 2019. 89:37–44. doi:10.1024/0300-9831/a000475 | Intervention/Exposure
53 | Mizgier, M, Jarzabek-Bielecka, G, Mruczyk, K. Maternal diet and gestational diabetes mellitus development. J Matern Fetal Neonatal Med. 2021. 34:77–86. doi:10.1080/14767058.2019.1598364 | Intervention/Exposure
54 | Nykjaer, C, Higgs, C, Greenwood, DC, Simpson, NAB, Cade, JE, Alwan, NA. Maternal fatty fish intake prior to and during pregnancy and risks of adverse birth outcomes: Findings from a british cohort. Nutrients. 2019. 11. doi:10.3390/nu11030643 | Intervention/Exposure
55 | O’Brien, CM, Louise, J, Deussen, A, Dodd, JM. In Overweight or Obese Pregnant Women, Maternal Dietary Factors are not Associated with Fetal Growth and Adiposity. Nutrients. 2018. 10. doi:10.3390/nu10070870 | Outcome
56 | Osorio-Yáñez, C, Gelaye, B, Qiu, C, Bao, W, Cardenas, A, Enquobahrie, DA, Williams, MA. Maternal intake of fried foods and risk of gestational diabetes mellitus. Ann Epidemiol. 2017. 27:384–390.e1. doi:10.1016/j.annepidem.2017.05.006 | Intervention/Exposure
57 | Parlapani, E, Agakidis, C, Karagiozoglou-Lampoudi, T, Sarafidis, K, Agakidou, E, Athanasiadis, A, Diamanti, E. The Mediterranean diet adherence by pregnant women delivering prematurely: association with size at birth and complications of prematurity. J Matern Fetal Neonatal Med. 2019. 32:1084–1091. doi:10.1080/14767058.2017.1399120 | Study Design
58 | Rohatgi, KW, Tinius, RA, Cade, WT, Steele, EM, Cahill, AG, Parra, DC. Relationships between consumption of ultra-processed foods, gestational weight gain and neonatal outcomes in a sample of US pregnant women. PeerJ. 2017. 5:e4091. doi:10.7717/peerj.4091 | Outcome
59 | Schoenaker, Dajm, Dodd, JM, Dodd, JM. Does preconception body mass index modify the effect of maternal diet on hypertensive disorders of pregnancy?. BJOG: An International Journal of Obstetrics & Gynaecology. 2019. 126:674–674. doi:10.1111/1471-0528.15596 | Publication Status
60 | Sen, Sarbattama, Rifas-Shiman, SherylL, Shivappa, Nitin, Wirth, MichaelD, Hebert, JamesR, Gold, DianeR, Gillman, MatthewW, Oken, Emily. Dietary Inflammatory Potential during Pregnancy Is Associated with Lower Fetal Growth and Breastfeeding Failure: Results from Project Viva. Journal of Clinical Chiropractic Pediatrics. 2017. 16:1381–1381. doi:10.3945/jn.115.225581 | Intervention/Exposure
61 | Simmons, D, Devlieger, R, van Assche, A, Jans, G, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Desoye, G, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, L, Lapolla, A, Dalfrà, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Snoek, FJ, Jelsma, JG, van Poppel, MN. Effect of Physical Activity and/or Healthy Eating on GDM Risk: The DALI Lifestyle Study. J Clin Endocrinol Metab. 2017. 102:903–913. doi:10.1210/jc.2016-3455 | Intervention/Exposure
62 | Simões-Wüst, AP, Moltó-Puigmartí, C, Jansen, EH, van Dongen, MC, Dagnelie, PC, Thijs, C. Organic food consumption during pregnancy and its association with health-related characteristics: the KOALA Birth Cohort Study. Public Health Nutr. 2017. 20:2145–2156. doi:10.1017/s1368980017001215 | Intervention/Exposure
63 | Starling, AP, Sauder, KA, Kaar, JL, Shapiro, AL, Siega-Riz, AM, Dabelea, D. Maternal Dietary Patterns during Pregnancy Are Associated with Newborn Body Composition. J Nutr. 2017. 147:1334–1339. doi:10.3945/jn.117.248948 | Confounders
64 | Stuart, JJ, Tanz, LJ, Missmer, SA, Rimm, EB, Spiegelman, D, James-Todd, TM, Rich-Edwards, JW. High Blood Pressure During Pregnancy and Development of Risk Factors for Cardiovascular Disease. Ann Intern Med. 2018. 169. doi:10.7326/p18-0008 | Study Design; Publication Status
65 | Tajima, Ryoko, Yachi, Yoko, Tanaka, Yasuhiro, Kawasaki, Yui Anasako, Nishibata, Izumi, Hirose, Ayumi Sugawara, Horikawa, Chika, Kodama, Satoru, Iida, Kaoruko, Sone, Hirohito. Carbohydrate intake during early pregnancy is inversely associated with abnormal glucose challenge test results in Japanese pregnant women. Diabetes/Metabolism Research & Reviews. 2017. 33:n/a-N.PAG. doi:10.1002/dmrr.2898 | Intervention/Exposure
66 | Tajirika-Shirai, R, Takimoto, H, Yokoyama, T, Kaneko, H, Kubota, T, Miyasaka, N. Effect of individualised dietary education at medical check-ups on maternal and fetal outcomes in pregnant Japanese women. Asia Pac J Clin Nutr. 2018. 27:607–616. doi:10.6133/apjcn.082017.01 | Study Design; Intervention/Exposure
67 | Tielemans, MJ, Erler, NS, Franco, OH, Jaddoe, VWV, Steegers, EAP, Kiefte-de Jong, JC. Dietary acid load and blood pressure development in pregnancy: The Generation R Study. Clin Nutr. 2018. 37:597–603. doi:10.1016/j.clnu.2017.01.013 | Intervention/Exposure
68 | Valkama, AJ, Meinilä, J, Koivusalo, S, Lindström, J, Rönö, K, Stach-Lempinen, B, Kautiainen, H, Eriksson, JG. The effect of pre-pregnancy lifestyle counselling on food intakes and association between food intakes and gestational diabetes in high-risk women: results from a randomised controlled trial. J Hum Nutr Diet. 2018. 31:301–305. doi:10.1111/jhn.12547 | Intervention/Exposure
69 | Valkama, AJ, Meinilä, JM, Koivusalo, SB, Lindström, J, Rönö, K, Stach-Lempinen, B, Eriksson, JG. Diet quality as assessed by the Healthy Food Intake Index and relationship with serum lipoprotein particles and serum fatty acids in pregnant women at increased risk for gestational diabetes. Br J Nutr. 2018. 120:914–924. doi:10.1017/s0007114518002404 | Confounders
70 | Van Der Hoeven, T, Browne, JL, Uiterwaal, CSPM, Van Der Ent, CK, Grobbee, DE, Dalmeijer, GW. Antenatal coffee and tea consumption and the effect on birth outcome and hypertensive pregnancy disorders. PLoS ONE. 2017. 12. doi:10.1371/journal.pone.0177619 | Intervention/Exposure
71 | Wu, Y, Sun, G, Zhou, X, Zhong, C, Chen, R, Xiong, T, Li, Q, Yi, N, Xiong, G, Hao, L, Yang, N, Yang, X. Pregnancy dietary cholesterol intake, major dietary cholesterol sources, and the risk of gestational diabetes mellitus: A prospective cohort study. Clin Nutr. 2020. 39:1525–1534. doi:10.1016/j.clnu.2019.06.016 | Intervention/Exposure
72 | Zareei, S, Homayounfar, R, Naghizadeh, MM, Ehrampoush, E, Rahimi, M. Dietary pattern in pregnancy and risk of gestational diabetes mellitus (GDM). Diabetes Metab Syndr. 2018. 12:399–404. doi:10.1016/j.dsx.2018.03.004 | Study Design
73 | Zhu, Y, Hedderson, MM, Sridhar, S, Xu, F, Feng, J, Ferrara, A. Poor diet quality in pregnancy is associated with increased risk of excess fetal growth: a prospective multi-racial/ethnic cohort study. Int J Epidemiol. 2019. 48:423–432. doi:10.1093/ije/dyy285 | Confounders
74 | Zulyniak, MA, de Souza, RJ, Shaikh, M, Desai, D, Lefebvre, DL, Gupta, M, Wilson, J, Wahi, G, Subbarao, P, Becker, AB, Mandhane, P, Turvey, SE, Beyene, J, Atkinson, S, Morrison, KM, McDonald, S, Teo, KK, Sears, MR, Anand, SS. Does the impact of a plant-based diet during pregnancy on birth weight differ by ethnicity? A dietary pattern analysis from a prospective Canadian birth cohort alliance. BMJ Open. 2017. 7:e017753. doi:10.1136/bmjopen-2017-017753 | Outcome

Table A 13 Search B articles excluded after full text screening

1 | Cardiometabolic benefits of balanced, time-restricted diet. Nursing. 2021. 51:19–19. doi:10.1097/01.NURSE.0000800112.56571.eb | Study Design; Publication Status
2 | High-Risk Coronary Plaque Regression After Intensive Lifestyle Intervention in Nonbstructive Coronary Disease: a Randomized Study. JACC. Cardiovascular imaging. 2020. doi:10.1016/j.jcmg.2020.10.019 | Health Status
3 | Vegetarian diets linked to reduced stroke risk. Canadian Nursing Home. 2020. 31:14–14. | Study Design; Publication Status
4 | Abbaspour, N, Roberts, T, Hooshmand, S, Kern, M, Hong, MY. Mixed nut consumption may improve cardiovascular disease risk factors in overweight and obese adults. Nutrients. 2019. 11. doi:10.3390/nu11071488 | Intervention/Exposure; Study Duration
5 | Abdrabalnabi, AA, Rajaram, S, Bitok, E, Oda, K, Beeson, WL, Kaur, A, Cofan, M, Serra-Mir, M, Roth, I, Ros, E, et al, . Effects of supplementing the usual diet with a daily dose of walnuts for two years on metabolic syndrome and its components in an elderly cohort. Nutrients. 2020. 12. doi:10.3390/nu12020451 | Intervention/Exposure
6 | Abe C, Imai T, Sezaki A, Miyamoto K, Kawase F, Shirai Y, Sanada M, Inden A, Kato T, Sugihara N, Shimokata H. Global Association between Traditional Japanese Diet Score and All-Cause, Cardiovascular Disease, and Total Cancer Mortality: A Cross-Sectional and Longitudinal Ecological Study. | Study Design
7 | Adachi, H, Enomoto, M, Fukami, A, Nakamura, S, Nohara, Y, Kono, S, Sakaue, A, Hamamura, H, Toyomasu, K, Yamamoto, M, Umeki, Y, Fukumoto, Y. Trends in nutritional intake and coronary risk factors over 60 years among Japanese men in Tanushimaru. Heart Vessels. 2020. 35:901–908. doi:10.1007/s00380-020-01561-9 | Intervention/Exposure
8 | Aekplakorn, W, Tantayotai, V, Numsangkul, S, Tatsato, N, Luckanajantachote, P, Himathongkam, T. Evaluation of a Community-Based Diabetes Prevention Program in Thailand: a Cluster Randomized Controlled Trial. Journal of primary care & community health. 2019. 10:2150132719847374. doi:10.1177/2150132719847374 | Intervention/Exposure
9 | Agostinis-Sobrinho C, Kievisiene J, Dubey V, Rauckiene-Michealsson A, Norkiene S, Ramirez-Velez R, Reuter CP, Brand C, Mota J, Santos R. Cardiovascular health behavior and blood pressure in adolescents: A longitudinal analysis. | Intervention/Exposure; Outcome; Comparator
10 | Ahc, Media. Vegetarians and Stroke. Neurology Alert. 2020. 39:1–2. | Publication Status
11 | Aiello P, Peluso I, Di Giacomo S, Di Sotto A, Villaño Valencia D. Body Composition and Metabolic Status of Italian and Spanish University Students: Relationship with Fruit and Vegetable Consumption. 14. | Study Design
12 | Akpulat, S, Gülsoy Kirnap, N, Pfeiffer, A. The effects of low-carbohydrate diet and protein-rich mixed diet on insulin sensitivity, basal metabolic rate and metabolic parameters in obese patients. Turkish Journal of Endocrinology and Metabolism. 2020. 24:206–213. doi:10.25179/tjem.2019-72200 | Study Design; Intervention/Exposure
13 | Akter, S, Mizoue, T, Nanri, A, Goto, A, Noda, M, Sawada, N, Yamaji, T, Iwasaki, M, Inoue, M, Tsugane, S, Tsugane, S, Sawada, N, Iwasaki, M, Ninue, M, Yamaji, T, Goto, A, Shimazu, TT, Charvat, H, Budhathoki, S, Muto, M, Suzuki, H, Miamizono, T, Kobayashi, Y, Iriei, M, Doi, M, Katagiri, M, Tagami, T, Sou, Y, Uehara, M, Hakubo, Y, Yamagishi, , Noda, M, Mizoue, T, Kawauchi, Y, Nakamura, K, Takachi, R, Ishihara, J, Iso, H, Sovue, T, Sito, I, Yasuda, N, Mimura, M, Sakata, K. Low carbohydrate diet and all cause and cause-specific mortality. Clinical Nutrition. 2021. 40:2016–2024. doi:10.1016/j.clnu.2020.09.022 | Intervention/Exposure
14 | Al Aamri, KS, Alrawahi, AH, Al Busaidi, N, Al Githi, MS, Al Jabri, K, Al Balushi, F, Ronquillo-Talara, R, Al Balushi, S, Waly, DM. The effect of low-carbohydrate ketogenic diet in the management of obesity compared with low caloric, low-fat diet. Clinical Nutrition ESPEN. 2022. | Intervention/Exposure
15 | Al Wattar H, B, Dodds, J, Placzek, A, Beresford, L, Spyreli, E, Moore, A, Gonzalez Carreras, FJ, Austin, F, Murugesu, N, Roseboom, TJ, Bes-Rastrollo, M, Hitman, GA, Hooper, R, Khan, KS, Thangaratinam, S. Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Medicine. 2019. 16. doi:10.1371/journal.pmed.1002857 | Data Overlap
16 | Al-Absi, HRH, Refaee, MA, Nazeemudeen, A, Househ, M, Shah, Z, Alam, T. Cardiovascular Diseases in Qatar: Smoking, Food Habits and Physical Activities Perspectives. Studies in health technology and informatics. 2020. 272:465–469. doi:10.3233/SHTI200596 | Study Design; Intervention/Exposure
17 | Alamolhoda, SH, Simbar, M, Mirmiran, P, Mirabi, P. Effect of low trans-fatty acid intakes on preeclampsia: A randomized controlled trial. J Res Med Sci. 2020. 25:112. doi:10.4103/jrms.JRMS_149_19 | Intervention/Exposure
18 | Albert SL, Massar RE, Correa L, Kwok L, Joshi S, Shah S, Boas R, Alcalá HE, McMacken M. Change in cardiometabolic risk factors in a pilot safety-net plant-based lifestyle medicine program. 10. | Study Design; Intervention/Exposure
19 | Aliashrafi, S, Arefhosseini, SR, Lotfi-Dizaji, L, Ebrahimi-Mameghani, M. Effect of vitamin D supplementation in combination with weight loss diet on lipid profile and sirtuin 1 in obese subjects with vitamin D deficiency: a double blind randomized clinical trial. Health Promot Perspect. 2019. 9:263–269. doi:10.15171/hpp.2019.36 | Intervention/Exposure
20 | Aljefree, NM, Almoraie, NM, Shatwan, IM. Association of two types of dietary pattern scores with cardiovascular disease risk factors and serum 25 hydroxy vitamin D levels in Saudi Arabia. Food Nutr Res. 2021. 65. doi:10.29219/fnr.v65.5481 | Study Design
21 | Al-Lahou B, Ausman LM, Peñalvo JL, Huggins GS, Zhang FF. Cardiometabolic deaths attributable to poor diet among Kuwaiti adults. 17. | Study Design
22 | Alonso Y, Miralles C, Algora MJ, Valiente-Pallejà A, Sánchez-Gistau V, Muntané G, Labad J, Vilella E, Martorell L. Risk factors for metabolic syndrome in individuals with recent-onset psychosis at disease onset and after 1-year follow-up. 12. | Study Design; Intervention/Exposure
23 | Alvarez-Alvarez, I, Toledo, E, Lecea, O, Salas-Salvado, J, Corella, D, Buil-Cosiales, P, Zomeno, MD, Vioque, J, Martinez, JA, Konieczna, J, Baron-Lopez, FJ, Lopez-Miranda, J, Estruch, R, Bueno-Cavanillas, A, Alonso-Gomez, AM, Tur, JA, Tinahones, FJ, Serra-Majem, L, Martin, V, OrtegaCalvo, M, Vazquez, C, Pinto, X, Vidal, J, Daimiel, L, Delgado-Rodriguez, M, Matia, P, Gonzalez, JI, Diaz-Lopez, A, Paz-Graniel, I, Munoz, MA, Fito, M, Pertusa-Martinez, S, Abete, I, Garcia-Rios, A, Ros, E, Ruiz-Canela, M, Martinez-Gonzalez, MA. Adherence to a priori dietary indexes and baseline prevalence of cardiovascular risk factors in the PREDIMED-Plus randomised trial. Eur J Nutr. 2020. 59:1219–1232. doi:10.1007/s00394-019-01982-x | Study Design
24 | Alves MA, Miranda AM, Cacau LT, Levy J, Generoso G, Bittencourt MS, Lotufo PA, Bensenor IM, Marchioni DM. Dietary patterns and subclinical atherosclerosis incidence and progression: Results from ELSA-Brasil. | Outcome
25 | Ambrosy AP, Malik UI, Leong TK, Allen AR, Sung SH, Go AS. Food security, diet quality, nutritional knowledge, and attitudes towards research in adults with heart failure during the COVID-19 pandemic. | Study Design; Health Status
26 | Amil, S, Lemieux, I, Poirier, P, Lamarche, B, Despres, JP, Almeras, N. Targeting Diet Quality at the Workplace: Influence on Cardiometabolic Risk. Nutrients. 2021. 13. doi:10.3390/nu13072283 | Study Design
27 | Andersen, E, van der Ploeg, HP, van Mechelen, W, Gray, CM, Mutrie, N, van Nassau, F, Jelsma, JGM, Anderson, AS, Silva, MN, Pereira, HV, McConnachie, A, Sattar, N, Sørensen, M, Røynesdal, ØB, Hunt, K, Roberts, GC, Wyke, S, Gill, JMR. Contributions of changes in physical activity, sedentary time, diet and body weight to changes in cardiometabolic risk. International Journal of Behavioral Nutrition and Physical Activity. 2021. 18. | Intervention/Exposure; Outcome
28 | Andueza, N, Cuervo, M, Martin-Calvo, N, Navas-Carretero, S. A nutritional intervention among children aged 6–12 years-old is effective on improving dietary pattern and anthropometry: randomized parallel controlled study. Annals of nutrition & metabolism. 2022. 78:38-. doi:10.1159/000526374 | Publication Status
29 | Anelli, GM, Parisi, F, Sarno, L, Fornaciari, O, Carlea, A, Coco, C, Porta, MD, Mollo, N, Villa, PM, Guida, M, Cazzola, R, Troiano, E, Pasotti, M, Volpi, G, Vetrani, L, Maione, M, Cetin, I. Associations between Maternal Dietary Patterns, Biomarkers and Delivery Outcomes in Healthy Singleton Pregnancies: Multicenter Italian GIFt Study. Nutrients. 2022. 14. | Outcome
30 | Angoorani, P, Mostafaei, S, Kiani, T, Ejtahed, H-S, Motlagh, ME, Shafiee, G, Gorabi, AM, Qorbani, M, Heshmat, R, Kelishadi, R. Determinants of childhood blood pressure using structure equation model: The CASPIAN-V study. BMC Cardiovascular Disorders. 2020. 20. | Study Design
31 | Antoniazzi, L, Arroyo-Olivares, R, Bittencourt, MS, Tada, MT, Lima, I, Jannes, CE, Krieger, JE, Pereira, AC, Quintana-Navarro, G, Muniz-Grijalvo, O, Diaz-Diaz, JL, Zambon, D, Mata, P, Santos, RD. Association of dietary components with dyslipidemia and low-grade inflammation biomarkers in adults with heterozygous familial hypercholesterolemia from different countries. Eur J Clin Nutr. 2019. 73:1622–1625. doi:10.1038/s41430-019-0529-3 | Study Design; Publication Status
32 | Appannah, G, Emi, NA, Gan, WY, Mohd Shariff, Z, Shamsuddin, NH, Anuar Zaini, A, Appukutty, M. The Relationships between a Dietary Pattern Linked to Cardiometabolic Risk Factors and Life Satisfaction in Early Adolescence. Int J Environ Res Public Health. 2020. 17. doi:10.3390/ijerph17155489 | Study Design; Outcome
33 | Arenaza, L, Medrano, M, Oses, M, Amasene, M, Diez, I, Rodriguez-Vigil, B, Labayen, I. The Effect of a Family-Based Lifestyle Education Program on Dietary Habits, Hepatic Fat and Adiposity Markers in 8–12-Year-Old Children with Overweight/Obesity. Nutrients. 2020. 12. doi:10.3390/nu12051443 | Intervention/Exposure; Comparator
34 | Arvizu, M, Afeiche, MC, Hansen, S, Halldorsson, TF, Olsen, SF, Chavarro, JE. Fat intake during pregnancy and risk of preeclampsia: a prospective cohort study in Denmark. European Journal of Clinical Nutrition. 2019. 73:1040–1048. doi:10.1038/s41430-018-0290-z | Intervention/Exposure
35 | Arvizu, M, Stuart, JJ, Rich-Edwards, JW, Gaskins, AJ, Rosner, B, Chavarro, JE. Prepregnancy adherence to dietary recommendations for the prevention of cardiovascular disease in relation to risk of hypertensive disorders of pregnancy. Am J Clin Nutr. 2020. 112:1429–1437. doi:10.1093/ajcn/nqaa214 | Life Stage
36 | Asemi, Z, Tabassi, Z, Samimi, M, Fahiminejad, T, Esmaillzadeh, A. Favourable effects of the Dietary Approaches to Stop Hypertension diet on glucose tolerance and lipid profiles in gestational diabetes: A randomised clinical trial. British Journal of Nutrition. 2013. 109:2024. | Health Status
37 | Asemi, Z, Tabassi, Z, Samimi, M, Fahiminejad, T, Esmaillzadeh, A. Favorable effects of the Dietary Approaches to Stop Hypertension diet on glucose tolerance and lipid profiles in gestational diabetes: a randomised clinical trial - Expression of concern. Br J Nutr. 2021. 1. doi:10.1017/S0007114521002002 | Study Design; Publication Status
38 | Asghari G, Mirmiran P, Rezaeemanesh A, Mahdavi M, Azizi F, Hadaegh F. Changes in ideal cardiovascular health among Iranian adolescents: 2007–2008 to 2015–2017. 22. | Study Design
39 | Assaf-Balut, C, de la Torre, NG, Durán, A, Bordiu, E, del Valle, L, Familiar, C, Valerio, J, Jimenez, I, Herraiz, MA, Izquierdo, N, Runkle, I, de Miguel, MP, Montañez, C, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. An early, universal mediterranean diet-based intervention in pregnancy reduces cardiovascular risk factors in the “fourth trimester”. Journal of Clinical Medicine. 2019. 8. doi:10.3390/jcm8091499 | Data Overlap
40 | Assaf-Balut, C, de la Torre, NG, Fuentes, M, Durán, A, Bordiú, E, Del Valle, L, Valerio, J, Jiménez, I, Herraiz, MA, Izquierdo, N, Torrejón, MJ, de Miguel, MP, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. A high adherence to six food targets of the mediterranean diet in the late first trimester is associated with a reduction in the risk of materno-foetal outcomes: The st. carlos gestational diabetes mellitus prevention study. Nutrients. 2019. 11. doi:10.3390/nu11010066 | Data Overlap
41 | Assaf-Balut, C, García De La Torre, N, Duran, A, Fuentes, M, Bordiú, E, Del Valle, L, Familiar, C, Valerio, J, Jiménez, I, Herraiz, MA, Izquierdo, N, Torrejon, MJ, Cuadrado, Á M, Ortega, I, Illana, FJ, Runkle, I, De Miguel, P, Moraga, I, Montañez, C, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. A mediterranean diet with an enhanced consumption of extra virgin olive oil and pistachios improves pregnancy outcomes in women without gestational diabetes mellitus: A sub-analysis of the St. Carlos gestational diabetes mellitus prevention study. Annals of Nutrition and Metabolism. 2019. 74:69–79. doi:10.1159/000495793 | Data Overlap
42 | Avnon, T, Paz Dubinsky, E, Lavie, I, Ben-Mayor Bashi, T, Anbar, R, Yogev, Y. The impact of a vegan diet on pregnancy outcomes. Journal of Perinatology. 2021. 41:1129–1133. doi:10.1038/s41372-020-00804-x | Confounders
43 | Azzini, E, Peluso, I, Intorre, F, Barnaba, L, Venneria, E, Foddai, MS, Ciarapica, D, Maiani, F, Raguzzini, A, Polito, A. Total and Plant Protein Consumption: The Role of Inflammation and Risk of Non-Communicable Disease. International Journal of Molecular Sciences. 2022. 23. | Study Design; Intervention/Exposure
44 | Bae, Y-J, Yu, K-W, Lee, K-H, Jang, K-I. Association of the healthy eating index with metabolic abnormalities among middle-aged adults living in single-person households in korea. Nutrients. 2021. 13. | Study Design
45 | Bahrami, A, Zarban, A, Dehghani, H, Mohamadifard, M, Tavallaie, S, Ferns, GA. The Relationship Between Adherence to a Dietary Approach to Stop Hypertension Diet with Oxidative Stress and Antioxidant Capacity in Young Women. Turkish Journal of Endocrinology and Metabolism. 2022. 26:141. | Study Design; Outcome
46 | Bakhtiari, A, Hajian-Tilaki, K, Omidvar, S, Nasiri-Amiri, F. Clinical and metabolic response to soy administration in older women with metabolic syndrome: A randomized controlled trial. Diabetology and Metabolic Syndrome. 2019. 11. doi:10.1186/s13098-019-0441-y | Intervention/Exposure
47 | Bakre S, Shea B, Langheier J, Hu EA. Blood Pressure Control in Individuals With Hypertension Who Used a Digital, Personalized Nutrition Platform: Longitudinal Study. 6. | Intervention/Exposure
48 | Baldwin, N, Bae, S, Ramachandran, R, VanWagner, LB, Jacobs, D, Terry, J, Shikany, J. DIETARY PATTERNS AND RISK OF NON-ALCOHOLIC FATTY LIVER DISEASE (NAFLD): A 25-YEAR FOLLOWUP FROM THE CORONARY ARTERY RISK DEVELOPMENT IN YOUNG ADULTS (CARDIA) STUDY Meagan Gray. Gastroenterology. 2021. 160:S-832. | Outcome; Publication Status
49 | Balkan, Lauren, Bryan, Joanna, Kim, Samuel, Sterling, Madeline, Brown, Todd, Judd, Suzanne, Hummel, Scott, Arora, Pankaj, Jackson, Elizabeth, Safford, Monika, Levitan, Emily, Goyal, Parag. THE DASH DIET PATTERN PROTECTS AGAINST INCIDENT HEART FAILURE. Journal of the American College of Cardiology (JACC). 2020. 75:721–721. doi:10.1016/S0735-1097(20)31348-6 | Publication Status
50 | Bansal S, Connolly M, Harder T. Impact of a Whole-Foods, Plant-Based Nutrition Intervention on Patients Living with Chronic Disease in an Underserved Community. 16. | Study Design
51 | Barker, Katelyn, Davy, Brenda. Is Consumption of Ultra-Processed Foods Associated with Cardiometabolic Risk?. Scan’s Pulse. 2021. 41:1–5. | Publication Status
52 | Barnard ND, Rembert E, Freeman A, Bradshaw M, Holubkov R, Kahleova H. Blood Type Is Not Associated with Changes in Cardiometabolic Outcomes in Response to a Plant-Based Dietary Intervention. 121. | Intervention/Exposure
53 | Barnard, ND, Alwarith, J, Rembert, E, Brandon, L, Nguyen, M, Goergen, A, Horne, T, do Nascimento, GF, Lakkadi, K, Tura, A, Holubkov, R, Kahleova, H. A Mediterranean Diet and Low-Fat Vegan Diet to Improve Body Weight and Cardiometabolic Risk Factors: A Randomized, Cross-over Trial. J Am Coll Nutr. 2021. 1–13. doi:10.1080/07315724.2020.1869625 | Intervention/Exposure
54 | Barnett JB, Zeng W. Healthy Eating for Successful Living in Older Adults™ community education program-evaluation of lifestyle behaviors: A randomized controlled trial. 3. | Intervention/Exposure; Study Duration; Outcome
55 | Barroso M, Zomeño MD, Díaz JL, Pérez S, Martí-Lluch R, Cordón F, Ramos R, Cabezas C, Salvador G, Castell C, Schröder H, Grau M. Efficacy of tailored recommendations to promote healthy lifestyles: a post hoc analysis of a randomized controlled trial. 11. | Intervention/Exposure
56 | Bartels ECM, den Braver NR, Borgonjen-van den Berg KJ, Rutters F, van der Heijden A, Beulens JWJ. Adherence to the Dutch healthy diet index and change in glycemic control and cardiometabolic markers in people with type 2 diabetes. | Health Status
57 | Basu A, Chien LC, Alman AC, Snell-Bergeon JK. Associations of dietary patterns and nutrients with coronary artery calcification and pericardial adiposity in a longitudinal study of adults with and without type 1 diabetes. 60. | Outcome
58 | Bayerle P, Beyer S, Tegtbur U, Kück M, Adel J, Kwast S, Pökel C, Kerling A, Busse M. Exercise Capacity, Iron Status, Body Composition, and Mediterranean Diet in Patients with Chronic Heart Failure. 15. | Study Design; Health Status
59 | Beasley, JM, Yi, SS, Ahn, J, Kwon, SC, Wylie-Rosett, J. Dietary Patterns in Chinese Americans are Associated with Cardiovascular Disease Risk Factors, the Chinese American Cardiovascular Health Assessment (CHA CHA). Journal of immigrant and minority health. 2019. 21:1061–1069. doi:10.1007/s10903-018-0800-z | Study Design
60 | Beigrezaei S, Jambarsang S, Khayyatzadeh SS, Mirzaei M, Mehrparvar AH, Salehi-Abargouei A. A comparison of principal component analysis, partial least-squares, and reduced-rank regressions in the identification of dietary patterns associated with hypertension: YaHS-TAMYZ and Shahedieh cohort studies. 9. | Study Design; Country
61 | Belardo D, Michos ED, Blankstein R, Blumenthal RS, Ferdinand KC, Hall K, Klatt K, Natajaran P, Ostfeld RJ, Reddy K, Rodriguez R, Sriram U, Tobias DK, Gulati M. Practical, Evidence-Based Approaches to Nutritional Modifications to Reduce Atherosclerotic Cardiovascular Disease: An American Society For Preventive Cardiology Clinical Practice Statement. 10. | Study Design
62 | Bellikci-Koyu E, Sarer-Yurekli BP, Karagozlu C, Aydin-Kose F, Ozgen AG, Buyuktuncer Z. Probiotic kefir consumption improves serum apolipoprotein A1 levels in metabolic syndrome patients: a randomized controlled clinical trial. 102. | Intervention/Exposure
63 | Benharrat, LI, Senouci, A, Benhabib, W, Mekki, K. Prevalence of metabolic syndrome in women with polycystic ovary syndrome: Relationship with lifestyle and cardiometabolic biomarkers. Romanian Journal of Diabetes, Nutrition and Metabolic Diseases. 2021. 28:383. | Study Design; Intervention/Exposure
64 | Ben-Yacov, O, Godneva, A, Rein, M, Shilo, S, Lotan-Pompan, M, Weinberger, A, Segal, E. Gut microbiome modulates the effects of a personalised postprandial-targeting (PPT) diet on cardiometabolic markers: a diet intervention in pre-diabetes. Gut. 2023. | Intervention/Exposure
65 | Bernabe-Ortiz, A, Pauschardt, J, Diez-Canseco, F, Miranda, JJ. Sustainability of mhealth effects on cardiometabolic risk factors: Five-year results of a randomized clinical trial. Journal of Medical Internet Research. 2020. 22. doi:10.2196/14595 | Intervention/Exposure
66 | Beydoun, HA, Huang, S, Beydoun, MA, Hossain, S, Zonderman, AB. Mediating-moderating effect of allostatic load on the association between dietary approaches to stop hypertension diet and all-cause and cause-specific mortality: 2001–2010 national health and nutrition examination surveys. Nutrients. 2019. 11. doi:10.3390/nu11102311 | Intervention/Exposure
67 | Bhave VM, Ament Z, Patki A, Gao Y, Kijpaisalratana N, Guo B, Chaudhary NS, Garcia Guarniz AL, Gerszten R, Correa A, Cushman M, Judd S, Irvin MR, Kimberly WT. Plasma metabolites link dietary patterns to stroke risk. | Intervention/Exposure; Outcome
68 | Bigornia SJ, Noel SE, Porter C, Zhang X, Talegawker SA, Carithers TC, Correa A, Tucker KL. Red meat consumption, incident cardiovascular disease, and the influence of dietary quality in the Jackson Heart Study. | Intervention/Exposure
69 | Blancas-Sánchez IM, Del Rosal Jurado M, Aparicio-Martínez P, Quintana Navarro G, Vaquero-Abellan M, Castro Jiménez RA, Fonseca Pozo FJ. A Mediterranean-Diet-Based Nutritional Intervention for Children with Prediabetes in a Rural Town: A Pilot Randomized Controlled Trial. 14. | Outcome
70 | Blumenthal, JA, Hinderliter, AL, Smith, PJ, Mabe, S, Watkins, LL, Craighead, L, Ingle, K, Tyson, C, Lin, P-H, Kraus, WE, Liao, L, Sherwood, A. Effects of Lifestyle Modification on Patients with Resistant Hypertension: Results of the TRIUMPH Randomized Clinical Trial. Circulation. 2021. 1212. | Intervention/Exposure; Health Status
71 | Bodnar LM, Cartus AR, Kennedy EH, Kirkpatrick SI, Parisi SM, Himes KP, Parker CB, Grobman WA, Simhan HN, Silver RM, Wing DA, Perry S, Naimi AI. A Doubly Robust Machine Learning-Based Approach to Evaluate Body Mass Index as a Modifier of the Association Between Fruit and Vegetable Intake and Preeclampsia. | Intervention/Exposure
72 | Bogataj Jontez N, Kenig S, Šik Novak K, Petelin A, Jenko Pražnikar Z, Mohorko N. Habitual low carbohydrate high fat diet compared with omnivorous, vegan, and vegetarian diets. 10. | Study Design; Intervention/Exposure
73 | Bonaccio M, Costanzo S, Di Castelnuovo A, Gialluisi A, Ruggiero E, De Curtis A, Persichillo M, Cerletti C, Donati MB, de Gaetano G, Iacoviello L. Increased adherence to the Mediterranean diet is associated with reduced low-grade inflammation after a 12.7-year period: results from the Moli-sani Study. | Outcome
74 | Bonaccio, M, Di Castelnuovo, A, Costanzo, S, De Curtis, A, Persichillo, M, Cerletti, C, Donati, MB, de Gaetano, G, Iacoviello, L. Impact of combined healthy lifestyle factors on survival in an adult general population and in high-risk groups: prospective results from the Moli-sani Study. Journal of Internal Medicine. 2019. 286:207–220. doi:10.1111/joim.12907 | Intervention/Exposure; Health Status
75 | Bowers, Jennifer. Nutrition Interventions to Manage Hyperlipidemia. Today’s Dietitian. 2020. 22:50–55. | Publication Status
76 | Bozbulut, R, Ertas-Ozturk, Y, Doger, E, Bideci, A, Koksal, E. Increased Obesity Awareness and Adherence to Healthy Lifestyle-Diet Reduce Metabolic Syndrome Risk in Overweight Children. J Am Coll Nutr. 2020. 39:432–437. doi:10.1080/07315724.2019.1691951 | Study Design
77 | Brand, C, Martins, CML, Lemes, VB, Pessoa, MLF, Dias, AF, Cadore, EL, Mota, J, Gaya, ACA, Gaya, AR. Effects and prevalence of responders after a multicomponent intervention on cardiometabolic risk factors in children and adolescents with overweight/obesity: Action for health study. J Sports Sci. 2020. 38:682–691. doi:10.1080/02640414.2020.1725384 | Intervention/Exposure
78 | Bruno, E, Oliverio, A, Paradiso, AV, Daniele, A, Tommasi, S, Tufaro, A, Terribile, DA, Magno, S, Filippone, A, Venturelli, E, Morelli, D, Baldassari, I, Cravana, ML, Manoukian, S, Pasanisi, P. A Mediterranean Dietary Intervention in Female Carriers of BRCA Mutations: Results from an Italian Prospective Randomized Controlled Trial. Cancers (Basel). 2020. 12. doi:10.3390/cancers12123732 | Intervention/Exposure
79 | Bruno, E, Roveda, E, Gargano, G, Baldassari, I, Oliverio, A, Galasso, L, Montaruli, A, Cortellini, M, Di Mauro, MG, Venturelli, E, Berrino, F, Pasanisi, P. Aderenza alle raccomandazioni WCRF/AICR 2018 e sonno in persone con sindrome metabolica. Epidemiologia e prevenzione. 2020. 44:288–294. doi:10.19191/EP20.4.P288.059 | Study Design
80 | Buchman, M, Jin, Q, Sotos-Prieto, M. The effectiveness of the Healthy Heart Score Intervention as a Primordial Prevention Tool in a Primary Care Setting: a Randomized Controlled Trial, Pilot Study. Revista espanola de nutricion humana y dietetica. 2019. 23:204–205. | Publication Status
81 | Buckland, G, Northstone, K, Emmett, PM, Taylor, CM. The inflammatory potential of the diet in childhood is associated with cardiometabolic risk in adolescence/young adulthood in the ALSPAC birth cohort. European Journal of Nutrition. 2022. 61:3471. | Intervention/Exposure
82 | Budhathoki, S, Sawada, N, Iwasaki, M, Yamaji, T, Goto, A, Kotemori, A, Ishihara, J, Takachi, R, Charvat, H, Mizoue, T, Iso, H, Tsugane, S, Japan Public Health Center-based Prospective Study, Group. Association of Animal and Plant Protein Intake With All-Cause and Cause-Specific Mortality in a Japanese Cohort. JAMA Intern Med. 2019. 179:1509–1518. doi:10.1001/jamainternmed.2019.2806 | Intervention/Exposure
83 | Cacau, LT, Benseñor, IM, Goulart, AC, Cardoso, LO, Lotufo, PA, Moreno, LA, Marchioni, DM. Adherence to the planetary health diet index and obesity indicators in the Brazilian longitudinal study of adult health (ELSA-Brasil). Nutrients. 2021. 13. | Study Design
84 | Caferoglu, Z, Erdal, B, Hatipoglu, N, Kurtoglu, S. The effects of diet quality and dietary acid load on insulin resistance in overweight children and adolescents. Los efectos de la calidad de la dieta y la carga ácida de la dieta sobre la resistencia a la insulina en niños y adolescentes con sobrepeso. 2022. 69:426. | Study Design
85 | Cai, Q, Duan, M-J, Dekker, LH, Carrero, JJ, Avesani, CM, Bakker, SJL, De Borst, MH, Navis, GJ. Ultraprocessed food consumption and kidney function decline in a population-based cohort in the Netherlands. American Journal of Clinical Nutrition. 2022. 116:263. | Outcome
86 | Cai, R, Chao, J, Li, D, Zhang, M, Kong, L, Wang, Y. Effect of community-based lifestyle interventions on weight loss and cardiometabolic risk factors in obese elderly in China: a randomized controlled trial. Experimental gerontology. 2019. 128:110749. doi:10.1016/j.exger.2019.110749 | Intervention/Exposure; Comparator
87 | Campanella, A, Iacovazzi, PA, Misciagna, G, Bonfiglio, C, Mirizzi, A, Franco, I, Bianco, A, Sorino, P, Caruso, MG, Cisternino, AM, Buongiorno, C, Liuzzi, R, Osella, AR. The Effect of Three Mediterranean Diets on Remnant Cholesterol and Non-Alcoholic Fatty Liver Disease: A Secondary Analysis. Nutrients. 2020. 12. doi:10.3390/nu12061674 | Intervention/Exposure
88 | Cao, Y, Liu, Y, Zhao, X, Duan, D, Dou, W, Fu, W, Chen, H, Bo, Y, Qiu, Y, Chen, G, Lyu, Q. Adherence to a Dietary Approaches to Stop Hypertension (DASH)-style Diet in Relation to Preeclampsia: A Case-Control Study. Sci Rep. 2020. 10:9078. doi:10.1038/s41598-020-65912-2 | Study Design
89 | Cao, Z, Xu, C, Yang, H, Li, S, Wang, Y. The Role of Healthy Lifestyle in Cancer Incidence and Temporal Transitions to Cardiometabolic Disease. JACC: CardioOncology. 2021. 3:663. | Health Status; Outcome; Comparator
90 | Carballo-Casla, A, Ortola, R, Garcia-Esquinas, E, Oliveira, A, Sotos-Prieto, M, Lopes, C, Lopez-Garcia, E, Rodriguez-Artalejo, F. The Southern European Atlantic Diet and all-cause mortality in older adults. BMC Med. 2021. 19:36. doi:10.1186/s12916-021-01911-y | Outcome
91 | Carubbi F, Alunno A, Mai F, Mercuri A, Centorame D, Cipolloni J, Mariani FM, Rossi M, Bartoloni E, Grassi D, Ferri C. Adherence to the Mediterranean diet and the impact on clinical features in primary Sjögren’s syndrome. 39 Suppl 133. | Study Design; Health Status
92 | Casas R, Ribó-Coll M, Ros E, Fitó M, Lamuela-Raventos RM, Salas-Salvadó J, Zazpe I, Martínez-González MA, Sorlí JV, Estruch R, Sacanella E. Change to a healthy diet in people over 70 years old: the PREDIMED experience. | Comparator
93 | Castela Forte J, Gannamani R, Folkertsma P, Kumaraswamy S, Mount S, van Dam S, Hoogsteen J. Changes in Blood Lipid Levels After a Digitally Enabled Cardiometabolic Preventive Health Program: Pre-Post Study in an Adult Dutch General Population Cohort. 6. | Study Design; Intervention/Exposure
94 | Castro-Acosta, ML, Sanders, TAB, Reidlinger, DP, Darzi, J, Hall, WL. Adherence to UK dietary guidelines is associated with higher dietary intake of total and specific polyphenols compared with a traditional UK diet: further analysis of data from the Cardiovascular risk REduction Study: supported by an Integrated Dietary Approach (CRESSIDA) randomised controlled trial. British journal of nutrition. 2019. 121:402–415. doi:10.1017/S0007114518003409 | Outcome
95 | Cesar, T, Benassi, R, Ponce, O, Nasser, M. Orange juice combined to a healthy-eating pattern improved endothelial function and reduced global risk of CHD in metabolic syndrome patients. Proceedings of the Nutrition Society. 2020. 79. doi:10.1017/S0029665120001895 | Publication Status; Comparator
96 | Cesari, F, Dinu, M, Pagliai, G, Rogolino, A, Giusti, B, Gori, AM, Casini, A, Marcucci, R, Sofi, F. Mediterranean, but not lacto-ovo-vegetarian, diet positively influence circulating progenitor cells for cardiovascular prevention: the CARDIVEG study. Nutrition, metabolism, and cardiovascular diseases : NMCD. 2019. 29:604–610. doi:10.1016/j.numecd.2019.02.005 | Intervention/Exposure; Outcome
97 | Chairistanidou C, Karatzi K, Karaglani E, Usheva N, Liatis S, Chakarova N, Mateo-Gallego R, Lamiquiz-Moneo I, Radó S, Antal E, Bíró É, Kivelä J, Wikström K, Iotova V, Cardon G, Makrilakis K, Manios Y. Diet quality in association to lipidaemic profile in adults of families at high-risk for type 2 diabetes in Europe: The Feel4Diabetes study. | Study Design
98 | Chan Q, Wren GM, Lau CE, Ebbels TMD, Gibson R, Loo RL, Aljuraiban GS, Posma JM, Dyer AR, Steffen LM, Rodriguez BL, Appel LJ, Daviglus ML, Elliott P, Stamler J, Holmes E, Van Horn L. Blood pressure interactions with the DASH dietary pattern, sodium, and potassium: The International Study of Macro-/Micronutrients and Blood Pressure (INTERMAP). | Study Design
99 | Chan, R, Leung, J, Woo, J. High Protein Intake Is Associated with Lower Risk of All-Cause Mortality in Community-Dwelling Chinese Older Men and Women. Journal of Nutrition, Health and Aging. 2019. 23:987–996. doi:10.1007/s12603-019-1263-1 | Intervention/Exposure; Country
100 | Chang, AR, Gummo, L, Yule, C, Bonaparte, H, Collins, C, Naylor, A, Appel, LJ, Juraschek, SP, Bailey-Davis, L. Effects of a Dietitian-Led, Telehealth Lifestyle Intervention on Blood Pressure: Results of a Randomized, Controlled Trial. Journal of the American Heart Association. 2022. e027213. | Intervention/Exposure; Comparator
101 | Chang, CM, Chiu, THT, Chang, CC, Lin, MN, Lin, CL. Plant-based diet, cholesterol, and risk of gallstone disease: A prospective study. Nutrients. 2019. 11. doi:10.3390/nu11020335 | Country
102 | Chang, SL, Lee, KJ, Nfor, ON, Chen, PH, Lu, WY, Ho, CC, Lung, CC, Chou, MC, Liaw, YP. Vegetarian Diets along with Regular Exercise: Impact on High-Density Lipoprotein Cholesterol Levels among Taiwanese Adults. Medicina (Kaunas). 2020. 56. doi:10.3390/medicina56020074 | Intervention/Exposure; Country
103 | Chang, SL, Nfor, ON, Ho, CC, Lee, KJ, Lu, WY, Lung, CC, Tantoh, DM, Hsu, SY, Chou, MC, Liaw, YP. Combination of Exercise and Vegetarian Diet: Relationship with High Density-Lipoprotein Cholesterol in Taiwanese Adults Based on MTHFR rs1801133 Polymorphism. Nutrients. 2020. 12. doi:10.3390/nu12061564 | Study Design; Intervention/Exposure
104 | Chen M, Xu Y, Wang X, Shan S, Cheng G. Association between the prudent dietary pattern and blood pressure in Chinese adults is partially mediated by body composition. 10. | Study Design
105 | Chen S, Zong G, Wu Q, Yun H, Niu Z, Zheng H, Zeng R, Sun L, Lin X. Associations of plasma glycerophospholipid profile with modifiable lifestyles and incident diabetes in middle-aged and older Chinese. 65. | Intervention/Exposure
106 | Chen, LW, Aubert, AM, Shivappa, N, Bernard, JY, Mensink-Bout, SM, Geraghty, AA, Mehegan, J, Suderman, M, Polanska, K, Hanke, W, Trafalska, E, Relton, CL, Crozier, SR, Harvey, NC, Cooper, C, Duijts, L, Heude, B, Hebert, JR, McAuliffe, FM, Kelleher, CC, Phillips, CM. Associations of maternal dietary inflammatory potential and quality with offspring birth outcomes: An individual participant data pooled analysis of 7 European cohorts in the ALPHABET consortium. PLoS Med. 2021. 18:e1003491. doi:10.1371/journal.pmed.1003491 | Outcome
107 | Chen, Xuanli, Chu, Jiadong, Hu, Wei, Sun, Na, He, Qida, Liu, Siyuan, Feng, Zhaolong, Li, Tongxing, Han, Qiang, Shen, Yueping. Associations of ultra-processed food consumption with cardiovascular disease and all-cause mortality: UK Biobank. European Journal of Public Health. 2022. 32:779–785. doi:10.1093/eurpub/ckac104 | Intervention/Exposure
108 | Chevli, PA, Mehta, A, Allison, M, Ding, J, Nasir, K, Blaha, MJ, Blankstein, R, Talegawkar, SA, Kanaya, AM, Shapiro, MD, Mongraw-Chaffin, M. Relationship of American Heart Association’s Life Simple 7, Ectopic Fat, and Insulin Resistance in 5 Racial/Ethnic Groups. Journal of Clinical Endocrinology and Metabolism. 2022. 107:E2394. | Study Design; Intervention/Exposure
109 | Chiu, THT, Chang, HR, Wang, LY, Chang, CC, Lin, MN, Lin, CL. Vegetarian diet and incidence of total, ischemic, and hemorrhagic stroke in 2 cohorts in Taiwan. Neurology. 2020. 94:e1112-e1121. doi:10.1212/WNL.0000000000009093 | Intervention/Exposure; Country
110 | Chiusolo, S, Aimo, A, Schmidt, EB, De Caterina, R. The ratio between n-3 and n-6 polyunsaturated fatty acids in the adipose tissue is more predictive of myocardial infarction than absolute levels of n-3 fatty acids: results from the danish diet, cancer and health cohort study. Giornale italiano di cardiologia. 2020. 21:e96-. | Intervention/Exposure
111 | Chiva-Blanch, G, Crespo, J, Estruch, R, Badimon, L. One year of mediterranean diet decreases microvesicle release from activated platelets and leukocytes in asymptomatic high cardiovascular risk patients. European heart journal. 2019. 40:8-. doi:10.1093/eurheartj/ehz747.0006 | Outcome; Publication Status
112 | Chmurzynska, A, Muzsik, A, Krzyżanowska-Jankowska, P, M. PPARG and FTO polymorphism can modulate the outcomes of a central European diet and a Mediterranean diet in centrally obese postmenopausal women. Nutrition Research. 2019. 69:94–100. doi:10.1016/j.nutres.2019.08.005 | Intervention/Exposure
113 | Choi MK, Park YM, Shivappa N, Hong OK, Han K, Steck SE, Hebert JR, Merchant AT, Sandler DP, Lee SS. Inflammatory potential of diet and risk of mortality in normal-weight adults with central obesity. 42. | Intervention/Exposure
114 | Choi, Y, Steffen, LM, Chu, H, Duprez, DA, Gallaher, DD, Shikany, JM, Schreiner, PJ, Shroff, GR, Jacobs, DR. A Plant-Centered Diet and Markers of Early Chronic Kidney Disease during Young to Middle Adulthood: Findings from the Coronary Artery Risk Development in Young Adults (CARDIA) Cohort. Journal of Nutrition. 2021. 151:2721. | Outcome
115 | Choi, YJ, Ailshire, JA, Kim, JK, Crimmins, EM. Diet Quality and Biological Risk in a National Sample of Older Americans. Journal of aging and health. 2021. 8982643211046818. | Outcome
116 | Chuang SY, Chang HY, Fang HL, Lee SC, Hsu YY, Yeh WT, Liu WL, Pan WH. The Healthy Taiwanese Eating Approach is inversely associated with all-cause and cause-specific mortality: A prospective study on the Nutrition and Health Survey in Taiwan, 1993–1996. 16. | Country
117 | Chudasama, YV, Khunti, K, Gillies, CL, Dhalwani, NN, Davies, MJ, Yates, T, Zaccardi, F. Healthy lifestyle and life expectancy in people with multimorbidity in the UK Biobank: A longitudinal cohort study. PLoS Med. 2020. 17:e1003332. doi:10.1371/journal.pmed.1003332 | Intervention/Exposure; Health Status; Outcome
118 | Cipryan L, Litschmannova M, Maffetone PB, Plews DJ, Dostal T, Hofmann P, Laursen PB. Very Low-Carbohydrate High-Fat Diet Improves Risk Markers for Cardiometabolic Health More Than Exercise in Men and Women With Overfat Constitution: Secondary Analysis of a Randomized Controlled Clinical Trial. 9. | Intervention/Exposure
119 | Cipryan, L, Dostal, T, Plews, DJ, Hofmann, P, Laursen, PB. Adiponectin/leptin ratio increases after a 12-week very low-carbohydrate, high-fat diet, and exercise training in healthy individuals: A non-randomized, parallel design study. Nutr Res. 2021. 87:22–30. doi:10.1016/j.nutres.2020.12.012 | Study Design; Intervention/Exposure
120 | Clark JS, Dyer KA, Davis CR, Shivappa N, Hébert JR, Woodman R, Hodgson JM, Murphy KJ. Adherence to a Mediterranean Diet for 6 Months Improves the Dietary Inflammatory Index in a Western Population: Results from the MedLey Study. 15. | Intervention/Exposure; Outcome
121 | Coates, AM, Morgillo, S, Yandell, C, Scholey, A, Buckley, JD, Dyer, KA, Hill, AM. Effect of a 12-Week Almond-Enriched Diet on Biomarkers of Cognitive Performance, Mood, and Cardiometabolic Health in Older Overweight Adults. Nutrients. 2020. 12. doi:10.3390/nu12041180 | Intervention/Exposure
122 | Cobos-Palacios L, Ruiz-Moreno MI, Vilches-Perez A, Vargas-Candela A, Muñoz-Úbeda M, Benítez Porres J, Navarro-Sanz A, Lopez-Carmona MD, Sanz-Canovas J, Perez-Belmonte LM, Mancebo-Sevilla JJ, Gomez-Huelgas R, Bernal-Lopez MR. Metabolically healthy obesity: Inflammatory biomarkers and adipokines in elderly population. 17. | Study Design
123 | Cockerham WC, Bauldry S, Sims M. Obesity-Related Health Lifestyles of Late-Middle Age Black Americans: The Jackson Heart Study. 63. | Study Design; Intervention/Exposure
124 | Comas Rovira M, Moreno Baró A, Burgaya Guiu N, Toledo Mesa L, Lesmes Heredia C, Pina Pérez S, Grimau Gallego M, Martí Malgosa L, Cochs Cosme B, Costa Pueyo J. The influence of obesity and diet quality on fetal growth and perinatal outcome. | Confounders
125 | Costa-Urrutia, P, Alvarez-Farina, R, Abud, C, Franco-Trecu, V, Esparza-Romero, J, Lopez-Morales, CM, Rodriguez-Arellano, ME, Valle Leal, J, Colistro, V, Granados, J. Effect of multi-component school-based program on body mass index, cardiovascular and diabetes risks in a multi-ethnic study. BMC Pediatr. 2019. 19:401. doi:10.1186/s12887-019-1787-x | Intervention/Exposure
126 | Costello E, Goodrich J, Patterson WB, Rock S, Li Y, Baumert B, Gilliland F, Goran MI, Chen Z, Alderete TL, Conti DV, Chatzi L. Diet Quality Is Associated with Glucose Regulation in a Cohort of Young Adults. 14. | Outcome
127 | Couch SC, Helsley RN, Siegel FU, Saelens BE, Magazine M, Eckman MH, Summer S, Fenchel M, King EC, Bhatt DL, Steen DL. Design and Rationale for the Supermarket and Web-Based Intervention Targeting Nutrition (SuperWIN) for Cardiovascular Risk Reduction Trial. | Study Design
128 | Couch, SC, Saelens, BE, Khoury, PR, Dart, KB, Hinn, K, Mitsnefes, MM, Daniels, SR, Urbina, EM. Dietary Approaches to Stop Hypertension Dietary Intervention Improves Blood Pressure and Vascular Health in Youth With Elevated Blood Pressure. Hypertension. 2021. 77:241–251. doi:10.1161/HYPERTENSIONAHA.120.16156 | Intervention/Exposure; Health Status
129 | Coura AGL, Arruda Neta ADCP, Lima RLFC, Bersch-Ferreira ÂC, Weber B, Vianna RPT. Tracking of Dietary Patterns in the Secondary Prevention of Cardiovascular Disease after a Nutritional Intervention Program-A Randomized Clinical Trial. 14. | Health Status
130 | Courtney, A, O’Brien, E, McAuliffe, F. The DASH (Dietary Approaches to Stop Hypertension) dietary pattern and blood pressure in pregnancy. BJOG. 2019. 126:42-. doi:10.1111/1471-0528.15633 | Study Design; Publication Status
131 | Crane, TE, Latif, YA, Wertheim, BC, Kohler, LN, Garcia, DO, Rhee, JJ, Seguin, R, Kazlauskaite, R, Shikany, JM, Thomson, CA. Does Season of Reported Dietary Intake Influence Diet Quality? Analysis from the Women’s Health Initiative. American Journal of Epidemiology. 2019. 188:1304–1310. doi:10.1093/aje/kwz087 | Outcome; Data Overlap
132 | Crovetto M, Sepúlveda MJ. Relationship between dietary energy intake, nutritional status and cardiovascular risk in adults from the communes of Quellón and Chonchi, Chiloé, Chile. 63. | Study Design
133 | Cuesta, M, Fuentes, M, Rubio, M, Bordiu, E, Barabash, A, Garcia de la Torre, N, Rojo-Martinez, G, Valdes, S, Soriguer, F, Vendrell, JJ, Urrutia, IM, Ortega, E, Montanya, E, Menendez, E, Lago-Sampedro, A, Gomis, R, Goday, A, Castell, C, Badia-Guillen, R, Girbes, J, Gaztambide, S, Franch-Nadal, J, Delgado Alvarez, E, Chaves, FJ, Castano, L, Calle-Pascual, AL. Incidence and regression of metabolic syndrome in a representative sample of the Spanish population: results of the cohort di@bet.es study. BMJ Open Diabetes Res Care. 2020. 8. doi:10.1136/bmjdrc-2020-001715 | Outcome
134 | Cui S, Yi K, Wu Y, Su X, Xiang Y, Yu Y, Tang M, Tong X, Zaid M, Jiang Y, Zhao Q, Zhao G. Fish Consumption and Risk of Stroke in Chinese Adults: A Prospective Cohort Study in Shanghai, China. 14. | Intervention/Exposure
135 | Curci, R, Bianco, A, Franco, I, Campanella, A, Mirizzi, A, Bonfiglio, C, Sorino, P, Fucilli, F, Di Giovanni, G, Giampaolo, N, Pesole, PL, Osella, AR. The Effect of Low Glycemic Index Mediterranean Diet and Combined Exercise Program on Metabolic-Associated Fatty Liver Disease: A Joint Modeling Approach. Journal of Clinical Medicine. 2022. 11. | Health Status; Comparator
136 | Cyr-Scully A, Howard AG, Sanzone E, Meyer KA, Du S, Zhang B, Wang H, Gordon-Larsen P. Characterizing the urban diet: development of an urbanized diet index. 21. | Study Design
137 | Czekajło, A, Różańska, D, Zatońska, K, Szuba, A, Regulska-Ilow, B. Association between dietary patterns and metabolic syndrome in the selected population of Polish adults-results of the PURE Poland Study. European journal of public health. 2019. 29:335–340. doi:10.1093/eurpub/cky207 | Study Design
138 | Damsgaard, CT, Papadaki, A, Jensen, SM, Ritz, C, Dalskov, S-M, Hlavaty, P, Saris, WHM, Martinez, JA, Handjieva-Darlenska, T, Andersen, MR, Stender, S, Larsen, TM, Astrup, A, M?lgaard, C, Michaelsen, KF. Higher protein diets consumed ad libitum improve cardiovascular risk markers in children of overweight parents from eight European countries. Journal of Nutrition. 2013. 143:810. | Intervention/Exposure
139 | Das A, Cumming R, Naganathan V, Blyth F, Couteur DGL, Handelsman DJ, Waite LM, Ribeiro RVR, Simpson SJ, Hirani V. Associations between dietary intake of total protein and sources of protein (plant vs. animal) and risk of all-cause and cause-specific mortality in older Australian men: The Concord Health and Ageing in Men Project. | Intervention/Exposure
140 | Das, SK, Bukhari, AS, Taetzsch, AG, Ernst, AK, Rogers, GT, Gilhooly, CH, Hatch-Mcchesney, A, Blanchard, CM, Livingston, KA, Silver, RE, Martin, E, McGraw, SM, Chin, MK, Vail, TA, Lutz, LJ, Montain, SJ, Pittas, AG, Lichtenstein, AH, Allison, DB, Dickinson, S, Chen, X, Saltzman, E, Young, AJ, Roberts, SB. Randomized trial of a novel lifestyle intervention compared with the Diabetes Prevention Program for weight loss in adult dependents of military service members. American Journal of Clinical Nutrition. 2021. 114:1546. | Intervention/Exposure
141 | de Almeida, VAH, da Costa, RA, Paganoti, CF, Mikami, FC, Sousa, AMDS, Peres, SV, Lopes, MAB, Francisco, RPV. Diet quality indices and physical activity levels associated with adequacy of gestational weight gain in pregnant women with gestational diabetes mellitus. Nutrients. 2021. 13. | Health Status
142 | De Giuseppe, R, Bocchi, M, Maffoni, S, Del Bo, E, Manzoni, F, Cerbo, RM, Porri, D, Cena, H. Mediterranean diet and lifestyle habits during pregnancy: Is there an association with small for gestational age infants? an italian single centre experience. Nutrients. 2021. 13. | Study Design; Outcome
143 | De La Torre, NG, Assaf-Balut, C, Varas, IJ, Del Valle, L, Durán, A, Fuentes, M, Del Prado, N, Bordiú, E, Valerio, JJ, Herraiz, MA, Izquierdo, N, Torrejón, MJ, Cuadrado, MA, De Miguel, P, Familiar, C, Runkle, I, Barabash, A, Rubio, MA, Calle-Pascual, AL. Effectiveness of following mediterranean diet recommendations in the real world in the incidence of gestational diabetes mellitus (Gdm) and adverse maternal-foetal outcomes: A prospective, universal, interventional study with a single group. the st carlos study. Nutrients. 2019. 11. doi:10.3390/nu11061210 | Study Design
144 | de Luis DA, Primo D, Izaola O, Aller R. Role of resistin (rs7139228) gene polymorphism with metabolic response after a hypocaloric mediterranean diet. | Intervention/Exposure; Comparator
145 | de Luis Roman, D, Primo, D, Izaola, O, Aller, R. Association of the APOA-5 Genetic Variant rs662799 with Metabolic Changes after an Intervention for 9 Months with a Low-Calorie Diet with a Mediterranean Profile. Nutrients. 2022. 14. | Intervention/Exposure
146 | de Luis, D, Izaola, O, Primo, D, Aller, R. A Randomized Trial with Two Hypocaloric Diets with Different Lipid Profiles and Effects on Serum Omentin-1 Levels in Obese Subjects. Disease markers. 2022. 2022:6777283. | Intervention/Exposure
147 | de Luis, DA, Izaola, O, Primo, D, Aller, R. Different effects of high-protein/low-carbohydrate versus standard hypocaloric diet on insulin resistance and lipid profile: Role of rs16147 variant of neuropeptide Y. Diabetes Research and Clinical Practice. 2019. 156. doi:10.1016/j.diabres.2019.107825 | Intervention/Exposure
148 | de Luis, DA, Primo, D, Izaola, O, Gomez Hoyos, E, Lopez Gomez, JJ, Ortola, A, Aller, R. Role of the variant in adiponectin gene rs266729 on weight loss and cardiovascular risk factors after a hypocaloric diet with the Mediterranean pattern. Nutrition. 2019. 60:1–5. doi:10.1016/j.nut.2018.08.018 | Study Design; Comparator
149 | de Luis, DA, Primo, D, Izaola, O, Gomez, E, Bachiller, R. Serum Lipid and Adiponectin Improvements after a Mediterranean Dietary Pattern in Non-G-Allele Carriers of the Variant rs3774261. Lifestyle Genom. 2020. 13:164–171. doi:10.1159/000508819 | Intervention/Exposure
150 | de Roos, Baukje, Wood, Sharon, Bremner, David, Bashir, Shabina, Betancor, MonicaB, Fraser, WilliamD, Duthie, SusanJ, Horgan, GrahamW, Sneddon, AlanA. The nutritional and cardiovascular health benefits of rapeseed oil-fed farmed salmon in humans are not decreased compared with those of traditionally farmed salmon: a randomized controlled trial. European Journal of Nutrition. 2021. 60:2063–2075. doi:10.1007/s00394-020-02396-w | Intervention/Exposure
151 | Dehghan, Mahshid, Mente, Andrew, Rangarajan, Sumathy, Mohan, Viswanathan, Lear, Scott, Swaminathan, Sumathi, Wielgosz, Andreas, Seron, Pamela, Avezum, Alvaro, Lopez-Jaramillo, Patricio, Turbide, Ginette, Chifamba, Jephat, AlHabib, KhalidF, Mohammadifard, Noushin, Szuba, Andrzej, Khatib, Rasha, Altuntas, Yuksel, Liu, Xiaoyun, Iqbal, Romaina, Rosengren, Annika. Association of egg intake with blood lipids, cardiovascular disease, and mortality in 177,000 people in 50 countries. American Journal of Clinical Nutrition. 2020. 111:795–803. doi:10.1093/ajcn/nqz348 | Intervention/Exposure
152 | Deierlein, AL, Ghassabian, A, Kahn, LG, Afanasyeva, Y, Mehta-Lee, SS, Brubaker, SG, Trasande, L. Dietary Quality and Sociodemographic and Health Behavior Characteristics Among Pregnant Women Participating in the New York University Children’s Health and Environment Study. Front Nutr. 2021. 8:639425. doi:10.3389/fnut.2021.639425 | Study Design; Outcome
153 | Di Renzo, L, Cinelli, G, Dri, M, Gualtieri, P, Attina, A, Leggeri, C, Cenname, G, Esposito, E, Pujia, A, Chiricolo, G, Salimei, C, De Lorenzo, A. Mediterranean Personalized Diet Combined with Physical Activity Therapy for the Prevention of Cardiovascular Diseases in Italian Women. Nutrients. 2020. 12. doi:10.3390/nu12113456 | Study Design; Intervention/Exposure
154 | Dibay Moghadam S, Navarro SL, Shojaie A, Randolph TW, Bettcher LF, Le CB, Hullar MA, Kratz M, Neuhouser ML, Lampe PD, Raftery D, Lampe JW. Plasma lipidomic profiles after a low and high glycemic load dietary pattern in a randomized controlled crossover feeding study. 16. | Study Duration
155 | Diez-Espino, J, Buil-Cosiales, P, Babio, N, Toledo, E, Corella, D, Ros, E, Fito, M, Gomez-Gracia, E, Estruch, R, Fiol, M, Lapetra, J, Alonso-Gomez, A, Serra-Majem, L, Pinto, X, Sorli, JV, Munoz, MA, Basora, J, Martinez-Gonzalez, MA. Impact of Life’s Simple 7 on the incidence of major cardiovascular events in high-risk Spanish adults in the PREDIMED study cohort. Rev Esp Cardiol (Engl Ed). 2020. 73:205–211. doi:10.1016/j.rec.2019.05.010 | Intervention/Exposure
156 | Dimitratos, SM, Hercules, M, Stephensen, CB, Cervantes, E, Laugero, KD. Association between physiological stress load and diet quality patterns differs between male and female adults. Physiology and Behavior. 2021. 240. doi:10.1016/j.physbeh.2021.113538 | Study Design
157 | Dimosthenopoulos, C, Hatziagelaki, E. The role of nutrition in the prevention of cardiovascular diseases. Diabetes, Stoffwechsel und Herz. 2019. 28:150–151. | Study Design; Publication Status
158 | Dimovski, K, Orho-Melander, M, Drake, I. A favorable lifestyle lowers the risk of coronary artery disease consistently across strata of non-modifiable risk factors in a population-based cohort. BMC Public Health. 2019. 19:1575. doi:10.1186/s12889-019-7948-x | Intervention/Exposure
159 | Ding M, Fitzmaurice GM, Arvizu M, Willett WC, Manson JE, Rexrode KM, Hu FB, Chavarro JE. Associations between patterns of modifiable risk factors in mid-life to late life and longevity: 36 year prospective cohort study. 1. | Outcome
160 | Ding, N, Wang, X, Tucker, KL, Weisskopf, MG, Sparrow, D, Hu, H, Park, SK. Dietary patterns, bone lead and incident coronary heart disease among middle-aged to elderly men. Environmental Research. 2019. 168:222–229. doi:10.1016/j.envres.2018.09.035 | Intervention/Exposure; Comparator
161 | Djuric, Zora, Rifkin, Samara. A New Score for Quantifying Adherence to a Cancer-Preventive Mediterranean Diet. Nutrition & Cancer. 2022. 74:579–591. doi:10.1080/01635581.2021.1909738 | Outcome
162 | Dodd, JM, Deussen, AR, Louise, J. A Randomised Trial to Optimise Gestational Weight Gain and Improve Maternal and Infant Health Outcomes through Antenatal Dietary, Lifestyle and Exercise Advice: The OPTIMISE Randomised Trial. Nutrients. 2019. 11. doi:10.3390/nu11122911 | Data Overlap
163 | Domènech, M, Serra-Mir, M, Roth, I, Freitas-Simoes, T, Valls-Pedret, C, Cofán, M, López, A, Sala-Vila, A, Calvo, C, Rajaram, S, Sabaté, J, Ros, E. Effect of a walnut diet on office and 24-hour ambulatory blood pressure in elderly individuals: Findings from the WAHA randomized trial. Hypertension. 2019. 73:1049–1057. doi:10.1161/HYPERTENSIONAHA.118.12766 | Intervention/Exposure
164 | Domínguez-López I, Arancibia-Riveros C, Casas R, Tresserra-Rimbau A, Razquin C, Martínez-González MÁ, Hu FB, Ros E, Fitó M, Estruch R, López-Sabater MC, Lamuela-Raventós RM. Changes in plasma total saturated fatty acids and palmitic acid are related to pro-inflammatory molecule IL-6 concentrations after nutritional intervention for one year. 150. | Study Design; Outcome
165 | Dorans, KS, Bazzano, LA, Qi, L, He, H, Chen, J, Appel, LJ, Chen, C-S, Hsieh, M-H, Hu, FB, Mills, KT, Nguyen, BT, O’Brien, MJ, Samet, JM, Uwaifo, GI, He, J. Effects of a Low-Carbohydrate Dietary Intervention on Hemoglobin A1c: A Randomized Clinical Trial. JAMA Network Open. 2022. 5:E2238645. | Intervention/Exposure
166 | Dos Santos K, Rosado EL, da Fonseca ACP, Belfort GP, da Silva LBG, Ribeiro-Alves M, Zembrzuski VM, Campos M Jr, Zajdenverg L, Drehmer M, Martínez JA, Saunders C. A Pilot Study of Dietetic, Phenotypic, and Genotypic Features Influencing Hypertensive Disorders of Pregnancy in Women with Pregestational Diabetes Mellitus. 13. | Intervention/Exposure
167 | Duan, MJ, Dekker, LH, Carrero, JJ, Navis, G. Blood lipids-related dietary patterns derived from reduced rank regression are associated with incident type 2 diabetes. Clin Nutr. 2021. 40:4712–4719. doi:10.1016/j.clnu.2021.04.046 | Outcome
168 | Ducharme-Smith K, Chambers R, Garcia-Larsen V, Larzelere F, Kenney A, Reid R, Nelson L, Richards J, Begay M, Barlow A, Rosenstock S. Native Youth Participating in the Together on Diabetes 12-Month Home-Visiting Program Reported Improvements in Alternative Healthy Eating Index-2010 Diet Quality Domains Likely to Be Associated With Blood Pressure and Glycemic Control. 121. | Study Design
169 | Dudum, R, Juraschek, SP, Appel, LJ. Dose-dependent effects of lifestyle interventions on blood lipid levels: Results from the PREMIER trial. Patient Education and Counseling. 2019. 102:1882–1891. doi:10.1016/j.pec.2019.05.005 | Intervention/Exposure
170 | Ebbeling, CB, Knapp, A, Johnson, A, Wong, JMW, Greco, KF, Ma, C, Mora, S, Ludwig, DS. Effects of a low-carbohydrate diet on insulin-resistant dyslipoproteinemia-a randomized controlled feeding trial. The American journal of clinical nutrition. 2021. | Intervention/Exposure
171 | Elliott LJ, Keown-Stoneman CDG, Birken CS, Jenkins DJA, Borkhoff CM, Maguire JL. Vegetarian Diet, Growth, and Nutrition in Early Childhood: A Longitudinal Cohort Study. | Intervention/Exposure
172 | Eriksen, R, Perez, IG, Posma, JM, Haid, M, Sharma, S, Prehn, C, Thomas, LE, Koivula, RW, Bizzotto, R, Prehn, C, Mari, A, Giordano, GN, Pavo, I, Schwenk, JM, De Masi, F, Tsirigos, KD, Brunak, S, Vinuela, A, Mahajan, A, McDonald, TJ, Kokkola, T, Rutter, F, Teare, H, Hansen, TH, Fernandez, J, Jones, A, Jennison, C, Walker, M, McCarthy, MI, Pedersen, O, Ruetten, H, Forgie, I, Bell, JD, Pearson, ER, Franks, PW, Adamski, J, Holmes, E, Frost, G. Dietary metabolite profiling brings new insight into the relationship between nutrition and metabolic risk: An IMI DIRECT study. EBioMedicine. 2020. 58:102932. doi:10.1016/j.ebiom.2020.102932 | Intervention/Exposure
173 | Estruch, R, Martínez-González, MA, Corella, D, Salas-Salvadó, J, Fitó, M, Chiva-Blanch, G, Fiol, M, Gómez-Gracia, E, Arós, F, Lapetra, J, Serra-Majem, L, Pintó, X, Buil-Cosiales, P, Sorlí, JV, Muñoz, MA, Basora-Gallisá, J, Lamuela-Raventós, RM, Serra-Mir, M, Ros, E. Effect of a high-fat Mediterranean diet on bodyweight and waist circumference: a prespecified secondary outcomes analysis of the PREDIMED randomised controlled trial. The Lancet Diabetes and Endocrinology. 2019. 7:e6-e17. doi:10.1016/S2213-8587(19)30074-9 | Outcome
174 | Estruch, Ramon, Sacanella, Emilio, Lamuela-Raventós, RosaM. Ideal Dietary Patterns and Foods to Prevent Cardiovascular Disease: Beware of Their Anti-Inflammatory Potential. Journal of the American College of Cardiology (JACC). 2020. 76:2194–2196. doi:10.1016/j.jacc.2020.09.575 | Publication Status
175 | Fagherazzi, S, Farias, DR, Belfort, GP, Dos Santos, K, Santana Vieira de Lima, T, Silva Dos Santos, M, Saunders, C. Impact of the Dietary Approaches to Stop Hypertension (DASH) diet on glycaemic control and consumption of processed and ultraprocessed foods in pregnant women with pre-gestational diabetes mellitus: a randomised clinical trial. Br J Nutr. 2021. 126:865–876. doi:10.1017/S0007114520004791 | Health Status; Outcome
176 | Falkenhain, K, Locke, SR, Lowe, DA, Reitsma, NJ, Lee, T, Singer, J, Weiss, EJ, Little, JP. Keyto app and device versus WW app on weight loss and metabolic risk in adults with overweight or obesity: A randomized trial. Obesity. 2021. 29:1606. | Intervention/Exposure
177 | Fang, Y, Xia, J, Lian, Y, Zhang, M, Kang, Y, Zhao, Z, Wang, L, Yin, P, Wang, Z, Ye, C, Zhou, M, He, Y. The burden of cardiovascular disease attributable to dietary risk factors in the provinces of China, 2002?2018: a nationwide population-based study. The Lancet Regional Health - Western Pacific. 2023. | Intervention/Exposure
178 | Farhadnejad, H, Asghari, G, Teymoori, F, Tahmasebinejad, Z, Mirmiran, P, Azizi, F. Low-carbohydrate diet and cardiovascular diseases in Iranian population: Tehran Lipid and Glucose Study. Nutrition, Metabolism and Cardiovascular Diseases. 2020. 30:581–588. doi:10.1016/j.numecd.2019.11.012 | Intervention/Exposure
179 | Feng HP, Yu PC, Huang SH, Huang YC, Chen CF, Sun CA, Wang BL, Chien WC, Chiang CH. The benefit of vegetarian diets for reducing blood pressure in Taiwan: a historically prospective cohort study. 42. | Study Design
180 | Fernandes AC, Marinho AR, Lopes C, Ramos E. Dietary glycemic load and its association with glucose metabolism and lipid profile in young adults. | Study Design; Intervention/Exposure
181 | Fernandez, CA, Potts, K, Bazzano, LA. Effect of ideal protein versus low-fat diet for weight loss: A randomized controlled trial. Obesity Science and Practice. 2021. | Intervention/Exposure
182 | Fernández-García, JC, Martínez-Sánchez, MA, Bernal-López, MR, Muñoz-Garach, A, Martínez-González, MA, Fitó, M, Salas-Salvadó, J, Tinahones, FJ, Ramos-Molina, B. Effect of a lifestyle intervention program with energy-restricted Mediterranean diet and exercise on the serum polyamine metabolome in individuals at high cardiovascular disease risk: A randomized clinical trial. American Journal of Clinical Nutrition. 2020. 111:975. | Intervention/Exposure; Comparator
183 | Fernandez-Lazaro, CI, Toledo, E, Buil-Cosiales, P, Salas-Salvadó, J, Corella, D, Fitó, M, Martínez, JA, Alonso-Gómez, ÁM, Wärnberg, J, Vioque, J, Romaguera, D, López-Miranda, J, Estruch, R, Tinahones, FJ, Lapetra, J, Serra-Majem, L, Bueno-Cavanillas, A, Tur, JA, Martín Sánchez, V, Pintó, X, Delgado-Rodríguez, M, Matía-Martín, P, Vidal, J, Ros, E, Vázquez, C, Daimiel, L, SanJulián, B, García-Gavilán, JF, Sorlí, JV, Castañer, O, Zulet, MÁ, Tojal-Sierra, L, Pérez-Farinós, N, Oncina-Canovas, A, Moñino, M, Garcia-Rios, A, Sacanella, E, Bernal-Lopez, RM, Santos-Lozano, JM, Vázquez-Ruiz, Z, Muralidharan, J, Ortega-Azorín, C, Goday, A, Razquin, C, Goicolea-Güemez, L, Ruiz-Canela, M, Becerra-Tomás, N, Schröder, H, Martínez González, MA. Factors associated with successful dietary changes in an energy-reduced Mediterranean diet intervention: a longitudinal analysis in the PREDIMED-Plus trial. European Journal of Nutrition. 2021. | Intervention/Exposure; Outcome
184 | Fernandez-Lazaro, CI, Toledo, E, Salas-Salvado, J, Corella, D, Fito, M, Martinez, JA, Buil-Cosiales, P. PREDIMED-Plus trial: one-year changes in the quality of dietary carbohydrate intake and concurrent changes in cardiovascular risk factors. Annals of nutrition & metabolism. 2019. 75:20–21. doi:10.1159/000501441 | Intervention/Exposure; Publication Status
185 | Fernández-Ruiz VE, Solé-Agustí M, Armero-Barranco D, Cauli O. Weight Loss and Improvement of Metabolic Alterations in Overweight and Obese Children Through the I(2)AO(2) Family Program: A Randomized Controlled Clinical Trial. 23. | Intervention/Exposure
186 | Ferro, Y, Mazza, E, Salvati, M, Santariga, E, Giampà, S, Spagnuolo, R, Doldo, P, Pujia, R, Coppola, A, Gazzaruso, C, Pujia, A, Montalcini, T. Effects of a portfolio-mediterranean diet and a mediterranean diet with or without a sterol-enriched yogurt in individuals with hypercholesterolemia. Endocrinology and Metabolism. 2020. 35:298–307. doi:10.3803/EnM.2020.35.2.298 | Study Duration
187 | Fiebel, PR, Ramachandra, SS, Holton, KF. The low glutamate diet reduces blood pressure in veterans with Gulf War Illness: A CONSORT randomized clinical trial. Medicine (United States). 2023. 102:E32726. | Intervention/Exposure
188 | Fleming, J, Kris-Etherton, P, Petersen, K, Baer, D. The dose-response effect of a mediterranean style diet with lean beef on lipids and lipoproteins. Circulation. 2019. 139. doi:10.1161/circ.139.suppl_1.045 | Study Duration; Publication Status
189 | Flor-Alemany M, Acosta-Manzano P, Migueles JH, Baena-García L, Aranda P, Aparicio VA. Association of Mediterranean diet adherence during pregnancy with maternal and neonatal lipid, glycemic and inflammatory markers: The GESTAFIT project. | Intervention/Exposure; Outcome
190 | Flor-Alemany M, Migueles JH, Acosta-Manzano P, Marín-Jiménez N, Baena-García L, Aparicio VA. Assessing the Mediterranean diet adherence during pregnancy: Practical considerations based on the associations with cardiometabolic risk. 31. | Intervention/Exposure; Outcome
191 | Francis EC, Dabelea D, Shankar K, Perng W. Maternal diet quality during pregnancy is associated with biomarkers of metabolic risk among male offspring. 64. | Outcome
192 | Franco AD, Morfino P, Aimo A. Plasma acylcarnitine, risk for heart failure or atrial fibrillation, and effects of the Mediterranean diet or obesity. | Study Design; Publication Status
193 | Fresán, U, Craig, WJ, Martínez-González, MA, Bes-Rastrollo, M. Nutritional quality and health effects of low environmental impact diets: The “seguimiento universidad de navarra” (sun) Cohort. Nutrients. 2020. 12:1–19. doi:10.3390/nu12082385 | Outcome
194 | Fresán, U, Martínez-González, MA, Sabaté, J, Bes-Rastrollo, M. Global sustainability (health, environment and monetary costs) of three dietary patterns: Results from a Spanish cohort (the SUN project). BMJ Open. 2019. 9. doi:10.1136/bmjopen-2018-021541 | Outcome
195 | Fung, TT, Li, Y, Bhupathiraju, SN, Bromage, S, Batis, C, Holmes, MD, Stampfer, M, Hu, FB, Deitchler, M, Willett, WC. Higher Global Diet Quality Score Is Inversely Associated with Risk of Type 2 Diabetes in US Women. Journal of Nutrition. 2021. 151:168S. | Outcome
196 | Fysekidis, M, Kesse-Guyot, E, Valensi, P, Arnault, N, Galan, P, Hercberg, S, Cosson, E. Association Between Adherence To The French Dietary Guidelines And Lower Resting Heart Rate, Longer Diastole Duration, And Lower Myocardial Oxygen Consumption. The NUTRIVASC Study. Vasc Health Risk Manag. 2019. 15:463–475. doi:10.2147/VHRM.S215795 | Outcome
197 | Gabiola, J, Morales, D, Quizon, O, Cadiz, RI, Feliciano, K, Ruiz, RL, Aguatis, CJ, Mararac, T, Rojina, J, Garcia, A, Hedlin, H, Cullen, M, Palaniappan, L. The EffectiveNess of LIfestyle with Diet and Physical Activity Education ProGram Among Prehypertensives and Stage 1 HyperTENsives in an Urban Community Setting (ENLIGHTEN) Study. J Community Health. 2020. 45:478–487. doi:10.1007/s10900-019-00764-0 | Intervention/Exposure
198 | Gadgil MD, Kanaya AM, Sands C, Chekmeneva E, Lewis MR, Kandula NR, Herrington DM. Diet Patterns Are Associated With Circulating Metabolites and Lipid Profiles of South Asians in the United States. | Outcome
199 | Gaeini, Z, Malmir, H, Mirmiran, P, Feizy, Z, Azizi, F. Snack consumption patterns and their associations with risk of incident metabolic syndrome: Tehran lipid and glucose study. Nutrition and Metabolism. 2023. 20. | Intervention/Exposure; Outcome
200 | Gainfort, A, Delahunt, A, Killeen, SL, O’Reilly, SL, H?bert, JR, Shivappa, N, McAuliffe, FM. Energy-Adjusted Dietary Inflammatory Index in pregnancy and maternal cardiometabolic health: findings from the ROLO study. AJOG Global Reports. 2023. 3. | Intervention/Exposure
201 | Gajda R, Raczkowska E, Sobieszczańska M, Noculak Ł, Szymala-Pędzik M, Godyla-Jabłoński M. Diet Quality Variation among Polish Older Adults: Association with Selected Metabolic Diseases, Demographic Characteristics and Socioeconomic Status. 20. | Study Design
202 | Gallardo-Escribano, C, Vargas-Candela, A, Vilches-Perez, A, Munoz-Melero, M, Ruiz-Moreno, MI, Benitez-Porres, J, Romance-Garcia, AR, Rodriguez-Ortega, R, Rosa-Lopez, A, Rosales-Jaime, A, Diaz-Ruiz, J, Tinahones, FJ, Gomez-Huelgas, R, Bernal-Lopez, MR. Lifestyle Modification Improves Insulin Resistance and Carotid Intima-Media Thickness in a Metabolically Healthy Obese Prepubescent Population. J Pediatr Gastroenterol Nutr. 2021. 72:127–134. doi:10.1097/MPG.0000000000002901 | Study Design
203 | Gao, J-W, Hao, Q-Y, Zhang, H-F, Li, X-Z, Yuan, Z-M, Guo, Y, Wang, J-F, Zhang, S-L, Liu, P-M. Low-carbohydrate diet score and coronary artery calcium progression. Arteriosclerosis, Thrombosis, and Vascular Biology. 2021. 41:491. | Intervention/Exposure
204 | Gao, JW, Hao, QY, Zhang, HF, Li, XZ, Yuan, ZM, Guo, Y, Wang, JF, Zhang, SL, Liu, PM. Low-Carbohydrate Diet Score and Coronary Artery Calcium Progression: Results From the CARDIA Study. Arterioscler Thromb Vasc Biol. 2021. 41:491–500. doi:10.1161/ATVBAHA.120.314838 | Intervention/Exposure; Outcome
205 | Garcia-Arellano, A, Martínez-González, MA, Ramallal, R, et al. Dietary inflammatory index and all-cause mortality in large cohorts: The SUN and PREDIMED studies. Clinical Nutrition. 2019. 38:1221–1231. doi:10.1016/j.clnu.2018.05.003 | Intervention/Exposure
206 | Garcia-Silva, J, Borrego, IRS, Navarrete, NN, Peralta-Ramirez, MI, Águila, FJ, Caballo, VE. Efficacy of cognitive-behavioural therapy for lifestyle modification in metabolic syndrome: a randomised controlled trial with a 18-months follow-up. Psychology & health. 2022. 1. | Intervention/Exposure; Comparator
207 | Garcia-Yu, IreneA, Garcia-Ortiz, Luis, Gomez-Marcos, ManuelA, Rodriguez-Sanchez, Emiliano, Agudo-Conde, Cristina, Gonzalez-Sanchez, Jesus, Maderuelo-Fernandez, JoseA, Recio-Rodriguez, JoseI. Effects of Cocoa-Rich Chocolate on Blood Pressure, Cardiovascular Risk Factors, and Arterial Stiffness in Postmenopausal Women: A Randomized Clinical Trial. Nutrients. 2020. 12:1758. doi:10.3390/nu12061758 | Intervention/Exposure; Comparator
208 | Gardner CD, Landry MJ, Perelman D, Petlura C, Durand LR, Aronica L, Crimarco A, Cunanan KM, Chang A, Dant CC, Robinson JL, Kim SH. Effect of a Ketogenic Diet versus Mediterranean Diet on HbA1c in Individuals with Prediabetes and Type 2 Diabetes Mellitus: the Interventional Keto-Med Randomized Crossover Trial. | Intervention/Exposure
209 | Garg PK, Wilson N, Levitan EB, Shikany JM, Howard VJ, Newby PK, Judd S, Howard G, Cushman M, Soliman EZ. Associations of dietary patterns with risk of incident atrial fibrillation in the REasons for Geographic And Racial Differences in Stroke (REGARDS). | Outcome
210 | Gargari G, Taverniti V, Del Bo’ C, Bernardi S, Hidalgo-Liberona N, Meroño T, Andres-Lacueva C, Kroon PA, Cherubini A, Riso P, Guglielmetti S. Higher bacterial DNAemia can affect the impact of a polyphenol-rich dietary pattern on biomarkers of intestinal permeability and cardiovascular risk in older subjects. 61. | Intervention/Exposure; Study Duration
211 | Garousi, N, Tamizifar, B, Pourmasoumi, M, Feizi, A, Askari, G, Clark, CCT, Entezari, MH. Effects of lacto-ovo-vegetarian diet vs. standard-weight-loss diet on obese and overweight adults with non-alcoholic fatty liver disease: a randomised clinical trial. Archives of physiology and biochemistry. 2021. 1–9. doi:10.1080/13813455.2021.1890128 | Health Status
212 | Garralda-Del-Villar, M, Carlos-Chillerón, S, Diaz-Gutierrez, J, Ruiz-Canela, M, Gea, A, Martínez-González, MA, Bes-Rastrollo, M, Ruiz-Estigarribia, L, Kales, SN, Fernández-Montero, A. Healthy lifestyle and incidence of metabolic syndrome in the SUN cohort. Nutrients. 2019. 11. doi:10.3390/nu11010065 | Intervention/Exposure; Outcome
213 | Geng T, Chang X, Wang L, Liu G, Jianjun L, Khor CC, Neelakantan N, Yuan JM, Koh WP, Pan A, Dorajoo R, Heng CK. The association of genetic susceptibility to smoking with cardiovascular disease mortality and the benefits of adhering to a DASH diet: The Singapore Chinese Health Study. | Intervention/Exposure; Outcome
214 | Genoni, G, Menegon, V, Monzani, A, Archero, F, Tagliaferri, F, Mancioppi, V, Peri, C, Bellone, S, Prodam, F. Healthy Lifestyle Intervention and Weight Loss Improve Cardiovascular Dysfunction in Children with Obesity. Nutrients. 2021. 13. doi:10.3390/nu13041301 | Study Design; Intervention/Exposure
215 | Georgoulis M, Yiannakouris N, Kechribari I, Lamprou K, Perraki E, Vagiakis E, Kontogianni MD. Sustained improvements in the cardiometabolic profile of patients with obstructive sleep apnea after a weight-loss Mediterranean diet/lifestyle intervention: 12-month follow-up (6 months post-intervention) of the “MIMOSA” randomized clinical trial. | Intervention/Exposure; Health Status
216 | Gepner, Y, Shelef, I, Komy, O, Cohen, N, Schwarzfuchs, D, Bril, N, Rein, M, Serfaty, D, Kenigsbuch, S, Zelicha, H, Yaskolka Meir, A, Tene, L, Bilitzky, A, Tsaban, G, Chassidim, Y, Sarusy, B, Ceglarek, U, Thiery, J, Stumvoll, M, Blüher, M, Stampfer, MJ, Rudich, A, Shai, I. The beneficial effects of Mediterranean diet over low-fat diet may be mediated by decreasing hepatic fat content. Journal of Hepatology. 2019. 71:379–388. doi:10.1016/j.jhep.2019.04.013 | Intervention/Exposure; Comparator
217 | Gerage, AM, Benedetti, TRB, Cavalcante, BR, Farah, BQ, Ritti-Dias, RM. Efficacy of a behavior change program on cardiovascular parameters in patients with hypertension: a randomized controlled trial. Einstein (Sao Paulo, Brazil). 2020. 18:eAO5227. doi:10.31744/einstein_journal/2020AO5227 | Intervention/Exposure; Health Status
218 | Gete, DG, Waller, M, Mishra, GD. Prepregnancy dietary patterns and risk of preterm birth and low birth weight: Findings from the Australian Longitudinal Study on Women’s Health. American Journal of Clinical Nutrition. 2020. 111:1048–1058. doi:10.1093/ajcn/nqaa057 | Outcome
219 | Gil-Campos M, Pérez-Ferreirós A, Llorente-Cantarero FJ, Anguita-Ruiz A, Bedoya-Carpente JJ, Kalén A, Moreno LA, Bueno G, Gil Á, Aguilera CM, Leis R. Association of Diet, Physical Activity Guidelines and Cardiometabolic Risk Markers in Children. 13. | Study Design
220 | Giosuè A, Recanati F, Calabrese I, Dembska K, Castaldi S, Gagliardi F, Vitale M, Vaccaro O, Antonelli M, Riccardi G. Good for the heart, good for the Earth: proposal of a dietary pattern able to optimize cardiovascular disease prevention and mitigate climate change. | Study Design; Outcome
221 | Giussani, M, Orlando, A, Tassistro, E, Lieti, G, Patti, I, Antolini, L, Parati, G, Genovesi, S. Impact of Lifestyle Modifications on Alterations in Lipid and Glycemic Profiles and Uric Acid Values in a Pediatric Population. Nutrients. 2022. 14. | Study Design; Intervention/Exposure
222 | Gkotzamanis, V, Panagiotakos, D, Yannakoulia, M, Kosmidis, M, Dardiotis, E, Hadjigeorgiou, G, Sakka, P, Scarmeas, N. Trajectories of healthy aging and their association with the Mediterranean diet: The HELIAD Study. Maturitas. 2022. 159:33. | Outcome
223 | Goff, LM, Huang, P, Silva, MJ, Bordoli, C, Enayat, EZ, Molaodi, OR, Cassidy, A, Maynard, M, Harding, S. Associations of dietary intake with cardiometabolic risk in a multi-ethnic cohort: A longitudinal analysis of the Determinants of Adolescence, now young Adults, Social well-being and Health (DASH) study. British Journal of Nutrition. 2019. 121:1069–1079. doi:10.1017/S0007114519000291 | Intervention/Exposure
224 | Gogga P, Sliwińska A, Aleksandrowicz-Wtona E, Malgorzewicz S. Lipid profile in Polish women following lacto-ovo-vegetarian and vegan diets - preliminary study. | Study Design
225 | Gómez-Sánchez, L, Rodríguez-Sánchez, E, Ramos, R, Marti-Lluch, R, Gómez-Sánchez, M, Lugones-Sánchez, C, Tamayo-Morales, O, Llamas-Ramos, I, Rigo, F, García-Ortiz, L, Gómez-Marcos, MA. The Association of Dietary Intake with Arterial Stiffness and Vascular Ageing in a Population with Intermediate Cardiovascular Risk—A MARK Study. Nutrients. 2022. 14. | Study Design; Outcome
226 | GomezSanchez, M, Gomez Sanchez, L, Patino-Alonso, MC, Alonso-Dominguez, R, Sanchez-Aguadero, N, Lugones-Sanchez, C, Rodriguez Sanchez, E, Garcia Ortiz, L, Gomez-Marcos, MA. Adherence to the Mediterranean Diet in Spanish Population and Its Relationship with Early Vascular Aging according to Sex and Age: EVA Study. Nutrients. 2020. 12. doi:10.3390/nu12041025 | Study Design; Outcome
227 | Gonçalves, AV, Pereira, RC, Bissoli, MC, Sanson, AL, Afonso, RJCF, de Angelis-Pereira, MC. Nutrition status and quantification of blood minerals by TXRF spectroscopy in vegetarian and non-vegetarian university students. Acta Scientiarum - Health Sciences. 2019. 41. doi:10.4025/actascihealthsci.v41i1.43065 | Study Design
228 | González, CarlosA, Bonet, Catalina, Pablo, Miguel de, Sanchez, María José, Salamanca-Fernandez, Elena, Dorronsoro, Miren, Amiano, Pilar, Huerta, Jose María, Chirlaque, María Dolores, Ardanaz, Eva, Barricarte, Aurelio, Quirós, Jose Ramón, Agudo, Antonio, Ferrer, Marta Guadalupe Rivera. Greenhouse gases emissions from the diet and risk of death and chronic diseases in the EPIC-Spain cohort. European Journal of Public Health. 2021. 31:130–135. doi:10.1093/eurpub/ckaa167 | Intervention/Exposure
229 | Granado-Casas, M, Martin, M, Martínez-Alonso, M, Alcubierre, N, Hernández, M, Alonso, N, Castelblanco, E, Mauricio, D. The mediterranean diet is associated with an improved quality of life in adults with type 1 diabetes. Nutrients. 2020. 12. doi:10.3390/nu12010131 | Health Status
230 | Grangeiro, ÉD, Trigueiro, MS, Siais, LO, Paiva, HM, Sola-Penna, M, Alves, MR, Rosado, EL. Hypocaloric diet with lower meal frequency did not affect weight loss, body composition and insulin responsiveness, but improved lipid profile: a randomized clinical trial. Food & function. 2021. 12:12594. | Intervention/Exposure
231 | Guo X, Xu X, Gao J, Wang W, Hou W, Wu X, Sun C, Li Y, Han T. Twenty-Year Trajectory-Patterns of Percentage Energy From Dietary Fat vs. Carbohydrate Throughout Adult Life and Associations With Cardio-Metabolic Disease and All-Cause Mortality. 8. | Intervention/Exposure; Country
232 | Guo, Fang, Zhang, Qiang, Yin, Yue, Liu, Yan, Jiang, Hong, Yan, Ni, Lin, Jing, Liu, Xiao-hong, Ma, Le. Legume consumption and risk of hypertension in a prospective cohort of Chinese men and women. British Journal of Nutrition. 2020. 123:564–573. doi:10.1017/S0007114519002812 | Intervention/Exposure
233 | Gürdeniz G, Uusitupa M, Hermansen K, Savolainen MJ, Schwab U, Kolehmainen M, Brader L, Cloetens L, Herzig KH, Hukkanen J, Rosqvist F, Ulven SM, Gunnarsdóttir I, Thorsdottir I, Oresic M, Poutanen KS, Risérus U, Åkesson B, Dragsted LO. Analysis of the SYSDIET Healthy Nordic Diet randomized trial based on metabolic profiling reveal beneficial effects on glucose metabolism and blood lipids. 41. | Intervention/Exposure
234 | Ha K, Nam K, Song Y. A moderate-carbohydrate diet with plant protein is inversely associated with cardiovascular risk factors: the Korea National Health and Nutrition Examination Survey 2013–2017. 19. | Study Design
235 | Ha, K, Kim, K, Sakaki, JR, Chun, OK. Relative Validity of Dietary Total Antioxidant Capacity for Predicting All-Cause Mortality in Comparison to Diet Quality Indexes in US Adults. Nutrients. 2020. 12. doi:10.3390/nu12051210 | Outcome
236 | Hailili, G, Chen, Z, Tian, T, Fu, WH, Pei, HL, Mahan, Y, Luo, T, Alimu, D, Wang, L, Zhang, GZ, Liu, LR, Wang, DL, Dai, JH. Dietary patterns and their associations with the metabolic syndrome and predicted 10-year risk of CVD in northwest Chinese adults. British Journal of Nutrition. 2021. 126:913–922. doi:10.1017/S000711452000478X | Study Design
237 | Ham, D, Cho, Y, Park, MS, Park, YS, Kim, SY, Seol, HM, Park, YM, Woo, S, Joung, H, Lim, DS. Inverse association of improved adherence to dietary guidelines with metabolic syndrome: the Seoul Metabolic Syndrome Management program. Nutr Res Pract. 2020. 14:621–636. doi:10.4162/nrp.2020.14.6.621 | Study Design; Intervention/Exposure; Outcome
238 | Han, L, Zhang, T, You, D, Chen, W, Bray, G, Sacks, F, Qi, L. Temporal and mediation relations of weight loss, and changes in insulin resistance and blood pressure in response to 2-year weight-loss diet interventions: the POUNDS Lost trial. European Journal of Nutrition. 2022. 61:269. | Intervention/Exposure
239 | Handzlik G, Szymańska E, Pękala E, Kędzierski L, Strzałkowska D, Duława J. Low-sodium dietary approach in the management of resistant and refractory hypertension: preliminary results. | Intervention/Exposure; Publication Status
240 | Hanley-Cook GT, Huybrechts I, Biessy C, Remans R, Kennedy G, Deschasaux-Tanguy M, Murray KA, Touvier M, Skeie G, Kesse-Guyot E, Argaw A, Casagrande C, Nicolas G, Vineis P, Millett CJ, Weiderpass E, Ferrari P, Dahm CC, Bueno-de-Mesquita HB, Sandanger TM, Ibsen DB, Freisling H, Ramne S, Jannasch F, van der Schouw YT, Schulze MB, Tsilidis KK, Tjønneland A, Ardanaz E, Bodén S, Cirera L, Gargano G, Halkjær J, Jakszyn P, Johansson I, Katzke V, Masala G, Panico S, Rodriguez-Barranco M, Sacerdote C, Srour B, Tumino R, Riboli E, Gunter MJ, Jones AD, Lachat C. Food biodiversity and total and cause-specific mortality in 9 European countries: An analysis of a prospective cohort study. 18. | Intervention/Exposure
241 | Hansen CD, Gram-Kampmann EM, Hansen JK, Hugger MB, Madsen BS, Jensen JM, Olesen S, Torp N, Rasmussen DN, Kjærgaard M, Johansen S, Lindvig KP, Andersen P, Thorhauge KH, Brønd JC, Hermann P, Beck-Nielsen H, Detlefsen S, Hansen T, Højlund K, Thiele MS, Israelsen M, Krag A. Effect of Calorie-Unrestricted Low-Carbohydrate, High-Fat Diet Versus High-Carbohydrate, Low-Fat Diet on Type 2 Diabetes and Nonalcoholic Fatty Liver Disease : A Randomized Controlled Trial. | Intervention/Exposure; Health Status
242 | Hardy, DS, Racette, SB, Garvin, JT, Gebrekristos, HT, Mersha, TB. Ancestry specific associations of a genetic risk score, dietary patterns and metabolic syndrome: a longitudinal ARIC study. BMC Med Genomics. 2021. 14:118. doi:10.1186/s12920-021-00961-8 | Outcome
243 | Harris S, Inoue S. Behavioral Counseling Interventions to Promote a Healthy Diet and Physical Activity for CVD Prevention in Adults Without CVD Risk Factors. 106. | Study Design
244 | Harvey, CJDC, Schofield, GM, Zinn, C, Thornley, SJ, Crofts, C, Merien, FLR. Low-carbohydrate diets differing in carbohydrate restriction improve cardiometabolic and anthropometric markers in healthy adults: A randomised clinical trial. PeerJ. 2019. 2019. doi:10.7717/peerj.6273 | Intervention/Exposure
245 | Hashem, A, Calderon, G, Silgado, MLR, Campos, A, Cifuentes, L, Franks, S, Mcrae, A, Burton, D, Acosta, A. THE IMPACT OF DIETARY CALORIC AND MACRONUTRIENTS COMPOSITION ON INTESTINAL CHOLESTEROL ABSORPTION, FECAL BILE AND FAT EXCRETION: A DEEPER INSIGHT INTO CHOLESTEROL METABOLISM IN HUMAN OBESITY. Gastroenterology. 2021. 160:S-740. | Study Duration; Publication Status
246 | Hashemi A, Vasquez K, Guishard D, Naji M, Ronning A, George-Alexander G, Vasquez D, Sylvester C, Pagano W, Khalida C, Coffran C, Ezeonu T, Fofana K, Bielopolski D, Vaughan R, Qureshi A, Tobin JN, Kost RG. Implementing DASH-aligned Congregate Meals and Self-Measured Blood Pressure in two senior centers: An open label study. | Intervention/Exposure
247 | Hassapidou, M, Tziomalos, K, Lazaridou, S, Pagkalos, I, Papadimitriou, K, Kokkinopoulou, A, Tzotzas, T. The Nutrition Health Alliance (NutriHeAl) Study: A Randomized, Controlled, Nutritional Intervention Based on Mediterranean Diet in Greek Municipalities. Journal of the American College of Nutrition. 2020. 39:338–344. doi:10.1080/07315724.2019.1660928 | Outcome
248 | Haywood, CJ, Prendergast, LA, Lim, R, Lappas, M, Lim, WK, Proietto, J. Obesity in older adults: Effect of degree of weight loss on cardiovascular markers and medications. Clinical Obesity. 2019. 9. doi:10.1111/cob.12316 | Intervention/Exposure; Comparator
249 | Hazrati Gonbad, Sara, Zakerimoghadam, Masoumeh, Pashaeypoor, Shahzad, Haghani, Shima. The Effects of Home-Based Self-Care Education on Blood Pressure and Self-Care Behaviors among Middle-Aged Patients with Primary Hypertension in Iran: A Randomized Clinical Controlled Trial. Home Health Care Management & Practice. 2022. 34:9–16. doi:10.1177/10848223211012727 | Study Duration
250 | He J, Yu S, Fang A, Shen X, Li K. Association between Protein Intake and the Risk of Hypertension among Chinese Men and Women: A Longitudinal Study. 14. | Intervention/Exposure
251 | He, D, Sun, N, Xiong, S, Qiao, Y, Ke, C, Shen, Y. Association between the proportions of carbohydrate and fat intake and hypertension risk: findings from the China Health and Nutrition Survey. Journal of hypertension. 2021. 39:1386–1392. doi:10.1097/HJH.0000000000002803 | Study Design; Intervention/Exposure; Country
252 | He, FJ, Campbell, NRC, Woodward, M, MacGregor, GA. Salt reduction to prevent hypertension: The reasons of the controversy. European Heart Journal. 2021. 42:2501–2505. doi:10.1093/eurheartj/ehab274 | Study Design; Intervention/Exposure
253 | He, M, Wang, J, Liang, Q, Li, M, Guo, H, Wang, Y, Deji, C, Sui, J, Wang, Y-W, Liu, Y, Zheng, Y, Qian, B, Chen, H, Ma, M, Su, S, Geng, H, Zhou, W-X, Guo, X, Zhu, W-Z, Zhang, M, Chen, Z, Rensen, PCN, Hui, C-C, Wang, Y, Shi, B. Time-restricted eating with or without low-carbohydrate diet reduces visceral fat and improves metabolic syndrome: A randomized trial. Cell reports. Medicine. 2022. 100777. | Intervention/Exposure
254 | He, Y, Fang, Y, Bromage, S, Fung, TT, Bhupathiraju, SN, Batis, C, Deitchler, M, Fawzi, W, Stampfer, MJ, Hu, FB, Willett, WC, Li, Y. Application of the Global Diet Quality Score in Chinese Adults to Evaluate the Double Burden of Nutrient Inadequacy and Metabolic Syndrome. Journal of Nutrition. 2021. 151:93S. | Study Design
255 | He, Y, Shen, J, He, X, Dong, X. Effects of community intervention and management on preventing and treating cardiovascular diseases among patients with dyslipidemia. International Journal of Clinical and Experimental Medicine. 2021. 14:1283. | Intervention/Exposure; Health Status
256 | Heianza, Y, Zhou, T, DiDonato, JA, Sun, Q, Rexrode, KM, Hu, FB, Bray, G, Sacks, FM, Manson, JE, Qi, L. Long-term changes in microbiota-dependent metabolite trimethylamine n-oxide and risks of hypertension and coronary heart disease, and their modulation by diet: the nurses’ health study and the pounds lost trial. Circulation. 2020. 141. doi:10.1161/circ.141.suppl_1.P205 | Intervention/Exposure; Publication Status
257 | Heianza, Y, Zhou, T, He, H, DiDonato, JA, Bray, GA, Sacks, FM, Qi, L. Changes in gut-microbiota-related metabolites and long-term improvements in lipoprotein subspecies in overweight and obese adults: the POUNDS lost trial. International Journal of Obesity. 2021. doi:10.1038/s41366-021-00939-7 | Intervention/Exposure
258 | Hejazi E, Emamat H, Sharafkhah M, Saidpour A, Poustchi H, Sepanlou S, Sotoudeh M, Dawsey S, Boffetta P, Abnet CC, Kamangar F, Etemadi A, Pourshams A, Malekshah AF, Berennan P, Malekzadeh R, Hekmatdoost A. Dietary acid load and mortality from all causes, CVD and cancer: results from the Golestan Cohort Study. 128. | Intervention/Exposure
259 | Hejazi, E, Emamat, H, Sharafkhah, M, Saidpour, A, Poustchi, H, Sepanlou, SG, Sotoudeh, M, Dawsey, SM, Boffetta, P, Abnet, CC, Kamangar, F, Etemadi, A, Pourshams, A, Fazeltabar-Malekshah, A, Brennan, P, Malekzadeh, R, Hekmatdoost, A. Dietary acid load and mortality from all causes, cardiovascular disease, and cancer: Results from the Golestan Cohort Study. British Journal of Nutrition. 2021. doi:10.1017/S0007114521003135 | Intervention/Exposure; Country
260 | Helk, O, Widhalm, K. Effects of a low-fat dietary regimen enriched with soy in children affected with heterozygous familial hypercholesterolemia. Clin Nutr ESPEN. 2020. 36:150–156. doi:10.1016/j.clnesp.2019.09.009 | Intervention/Exposure
261 | Henríquez-Sánchez, P, Sánchez-Villegas, A, Ruano-Rodríguez, C, Gea, A, Lamuela-Raventós, RM, Estruch, R, Salas-Salvadó, J, Covas, MI, Corella, D, Schröder, H, Gutiérrez-Bedmar, M, Santos-Lozano, JM, Pintó, X, Arós, F, Fiol, M, Tresserra-Rimbau, A, Ros, E, Martínez-González, MA, Serra-Majem, L. Dietary total antioxidant capacity and mortality in the PREDIMED study. European Journal of Nutrition. 2016. 55:227. | Intervention/Exposure
262 | Hernaez, A, Castaner, O, Tresserra-Rimbau, A, Pinto, X, Fito, M, Casas, R, Martinez-Gonzalez, MA, Corella, D, Salas-Salvado, J, Lapetra, J, Gomez-Gracia, E, Aros, F, Fiol, M, Serra-Majem, L, Ros, E, Estruch, R. Mediterranean Diet and Atherothrombosis Biomarkers: A Randomized Controlled Trial. Mol Nutr Food Res. 2020. 64:e2000350. doi:10.1002/mnfr.202000350 | Outcome
263 | Hernáez, Á, Sanllorente, A, Castañer, O, Martínez-González, Á M, Ros, E, Pintó, X, Estruch, R, Salas-Salvadó, J, Corella, D, Alonso-Gómez, ÁM, Serra-Majem, L, Fiol, M, Lapetra, J, Gómez-Gracia, E, de la Torre, R, Lamuela-Raventós, RM, Fitó, M. Increased Consumption of Virgin Olive Oil, Nuts, Legumes, Whole Grains, and Fish Promotes HDL Functions in Humans. Molecular nutrition & food research. 2019. 63:e1800847. doi:10.1002/mnfr.201800847 | Intervention/Exposure
264 | Hernández-Alonso, P, Giardina, S, Cañueto, D, Salas-Salvadó, J, Cañellas, N, Bulló, M. Changes in Plasma Metabolite Concentrations after a Low-Glycemic Index Diet Intervention. Molecular nutrition & food research. 2019. 63:e1700975. doi:10.1002/mnfr.201700975 | Intervention/Exposure
265 | Hernández-Hernández A, Oliver D, Martínez-González MÁ, Ruiz-Canela M, Eguaras S, Toledo E, de la Rosa PA, Bes-Rastrollo M, Gea A. Mediterranean Alcohol-Drinking Pattern and Arterial Hypertension in the “Seguimiento Universidad de Navarra” (SUN) Prospective Cohort Study. 15. | Intervention/Exposure
266 | Hernando-Redondo J, Toloba A, Benaiges D, Salas-Salvadó J, Martínez-Gonzalez MA, Corella D, Estruch R, Tinahones FJ, Ros E, Goday A, Castañer O, Fitó M. Mid- and long-term changes in satiety-related hormones, lipid and glucose metabolism, and inflammation after a Mediterranean diet intervention with the goal of losing weight: A randomized, clinical trial. 9. | Intervention/Exposure
267 | Hill EB, Siebert JC, Yazza DN, Ostendorf DM, Bing K, Wayland L, Scorsone JJ, Bessesen DH, MacLean PS, Melanson EL, Catenacci VA, Borengasser SJ. Proteomics, dietary intake, and changes in cardiometabolic health within a behavioral weight-loss intervention: A pilot study. 30. | Intervention/Exposure; Comparator
268 | Hillesheim E, Yin X, Sundaramoorthy GP, Brennan L. Using a metabotype framework to deliver personalised nutrition improves dietary quality and metabolic health parameters: A 12-week randomised controlled trial. | Intervention/Exposure; Comparator
269 | Ho, FK, Gray, SR, Welsh, P, Petermann-Rocha, F, Foster, H, Waddell, H, Anderson, J, Lyall, D, Sattar, N, Gill, JMR, Mathers, JC, Pell, JP, Celis-Morales, C. Associations of fat and carbohydrate intake with cardiovascular disease and mortality: prospective cohort study of UK Biobank participants. BMJ. 2020. 368:m688. doi:10.1136/bmj.m688 | Intervention/Exposure
270 | Hoevenaars, FPM, Esser, D, Schutte, S, Priebe, MG, Vonk, RJ, Van Den Brink, WJ, Van Der Kamp, JW, Stroeve, JHM, Afman, LA, Wopereis, S. Whole Grain Wheat Consumption Affects Postprandial Inflammatory Response in a Randomized Controlled Trial in Overweight and Obese Adults with Mild Hypercholesterolemia in the Graandioos Study. Journal of Nutrition. 2019. 149:2133–2144. doi:10.1093/jn/nxz177 | Intervention/Exposure
271 | Hosseinpour-Niazi S, Mirmiran P, Hadaegh F, Daneshpour MS, Hedayati M, Azizi F. The effect of TCF7L2 polymorphisms on inflammatory markers after 16 weeks of legume-based dietary approach to stop hypertension (DASH) diet versus a standard DASH diet: a randomised controlled trial. 19. | Health Status
272 | Hritani R. Heart healthy diet: A modifiable tool for cardiovascular disease prevention. 8. | Publication Status
273 | Hu, T, Jacobs, DR, Bazzano, LA, Bertoni, AG, Steffen, LM. Low-carbohydrate diets and prevalence, incidence and progression of coronary artery calcium in the Multi-Ethnic Study of Atherosclerosis (MESA). British Journal of Nutrition. 2019. 121:461–468. doi:10.1017/S0007114518003513 | Outcome
274 | Huang, CH, Okada, K, Matsushita, E, Uno, C, Satake, S, Arakawa Martins, B, Kuzuya, M. Dietary Patterns and Muscle Mass, Muscle Strength, and Physical Performance in the Elderly: A 3-Year Cohort Study. J Nutr Health Aging. 2021. 25:108–115. doi:10.1007/s12603-020-1437-x | Outcome
275 | Huang, L, Shang, L, Yang, W, Li, D, Qi, C, Xin, J, Wang, S, Yang, L, Zeng, L, Chung, MC. High starchy food intake may increase the risk of adverse pregnancy outcomes: a nested case-control study in the Shaanxi province of Northwestern China. BMC Pregnancy Childbirth. 2019. 19:362. doi:10.1186/s12884-019-2524-z | Outcome
276 | Hubacek, JA, Nikitin, Y, Ragino, Y, Stakhneva, E, Pikhart, H, Peasey, A, Holmes, MV, Stefler, D, Ryabikov, A, Verevkin, E, Bobak, M, Malyutina, S. Longitudinal trajectories of blood lipid levels in an ageing population sample of Russian Western-Siberian urban population. PLoS ONE. 2021. 16. | Intervention/Exposure
277 | Hudson, JL, Zhou, J, Kim, JE, Campbell, WW. Incorporating Milk Protein Isolate into an Energy-Restricted Western-Style Eating Pattern Augments Improvements in Blood Pressure and Triglycerides, but Not Body Composition Changes in Adults Classified as Overweight or Obese: A Randomized Controlled Trial. Nutrients. 2020. 12. doi:10.3390/nu12030851 | Intervention/Exposure
278 | Hunter, SR, Considine, RV, Mattes, RD. Almond consumption decreases android fat mass percentage in adults with high android subcutaneous adiposity but does not change HbA1c in a randomised controlled trial. British Journal of Nutrition. 2022. 127:850. | Intervention/Exposure
279 | Ikem, E, Halldorsson, TI, Birgisdóttir, BE, Rasmussen, MA, Olsen, SF, Maslova, E. Dietary patterns and the risk of pregnancy-associated hypertension in the Danish National Birth Cohort: a prospective longitudinal study. BJOG: An International Journal of Obstetrics and Gynaecology. 2019. 126:663–673. doi:10.1111/1471-0528.15593 | Data Overlap
280 | Innocenti, A, Fusi, J, Cammisuli, DM, Franzoni, F, Galetta, F, Pruneti, C. Effects of Mediterranean diet and weight loss on blood-lipid profile in overweight adults with hypercholesterolemia. Progress in Nutrition. 2019. 21:889–899. doi:10.23751/pn.v21i4.8089 | Study Design; Intervention/Exposure
281 | Ivanova, OS, Maychuk, EY, Voevodina, IV. Assessment of risk factors of cardiovascular diseases and arterial stiffness in women of different ages. Russian Archives of Internal Medicine. 2020. 10:139–147. doi:10.20514/2226-6704-2020-10-2-139-147 | Study Design; Intervention/Exposure; Comparator
282 | Izaola O, Primo D, de Luis D. Dietary Intervention during 9 Months with a Hypocaloric Diet, Interaction of the Genetic Variant of Adiponectin Gene rs822393 with Metabolic Parameters. 2022. | Study Design; Intervention/Exposure
283 | Jack-Roberts, C, Maples, P, Kalkan, B, Edwards, K, Gilboa, E, Djuraev, I, Zou, S, Hoepner, L, Fordjour, L, Lee, WC, Kral, J, Dalloul, M, Jiang, X. Gestational diabetes status and dietary intake modify maternal and cord blood allostatic load markers. BMJ Open Diabetes Research and Care. 2020. 8. doi:10.1136/bmjdrc-2020-001468 | Intervention/Exposure; Outcome
284 | Jakse, B, Jakse, B, Pinter, S, Jug, B, Godnov, U, Pajek, J, Fidler Mis, N. Dietary Intakes and Cardiovascular Health of Healthy Adults in Short-, Medium-, and Long-Term Whole-Food Plant-Based Lifestyle Program. Nutrients. 2019. 12. doi:10.3390/nu12010055 | Study Design
285 | Jannasch F, Nickel DV, Bergmann MM, Schulze MB. A New Evidence-Based Diet Score to Capture Associations of Food Consumption and Chronic Disease Risk. 14. | Study Design
286 | Jaspers Faijer-Westerink, H, Stavnsbo, M, Hutten, BA, Chinapaw, M, Vrijkotte, TGM. Ideal cardiovascular health at age 5–6 years and cardiometabolic outcomes in preadolescence. Int J Behav Nutr Phys Act. 2021. 18:33. doi:10.1186/s12966-021-01090-2 | Intervention/Exposure; Outcome
287 | Jayanama, K, Theou, O, Godin, J, Cahill, L, Shivappa, N, Hebert, JR, Wirth, MD, Park, YM, Fung, TT, Rockwood, K. Relationship between diet quality scores and the risk of frailty and mortality in adults across a wide age spectrum. BMC Med. 2021. 19:64. doi:10.1186/s12916-021-01918-5 | Outcome
288 | Jenkins, DJA, Jones, PJH, Lamarche, B, Kendall, CWC, Faulkner, D, Cermakova, L, Gigleux, I, Ramprasath, V, De Souza, R, Ireland, C, Patel, D, Srichaikul, K, Abdulnour, S, Bashyam, B, Collier, C, Hoshizaki, S, Josse, RG, Leiter, LA, Connelly, PW, Frohlich, J. Effect of a dietary portfolio of cholesterol-lowering foods given at 2 levels of intensity of dietary advice on serum lipids in hyperlipidemia: A randomized controlled trial. JAMA. 2011. 306:831. | Intervention/Exposure
289 | Jenkins, DJA, Dehghan, M, Mente, A, Bangdiwala, SI, Rangarajan, S, Srichaikul, K, Mohan, V, Avezum, A, Diaz, R, Rosengren, A, Lanas, F, Lopez-Jaramillo, P, Li, W, Oguz, A, Khatib, R, Poirier, P, Mohammadifard, N, Pepe, A, Alhabib, KF, Chifamba, J, Yusufali, AH, Iqbal, R, Yeates, K, Yusoff, K, Ismail, N, Teo, K, Swaminathan, S, Liu, X, Zatonska, K, Yusuf, R, Yusuf, S, Pure Study Investigators. Glycemic Index, Glycemic Load, and Cardiovascular Disease and Mortality. N Engl J Med. 2021. 384:1312–1322. doi:10.1056/NEJMoa2007123 | Intervention/Exposure
290 | Jennings, A, Berendsen, AM, de Groot, Lcpgm, Feskens, EJM, Brzozowska, A, Sicinska, E, Pietruszka, B, Meunier, N, Caumon, E, Malpuech-Brugère, C, etal, . Mediterranean-Style Diet Improves Systolic Blood Pressure and Arterial Stiffness in Older Adults. Hypertension (dallas, tex. : 1979). 2019. 73:578–586. doi:10.1161/HYPERTENSIONAHA.118.12259 | Intervention/Exposure
291 | Jessri M, Hennessey D, Eddeen AB, Bennett C, Sanmartin C, Manuel D. Dietary Patterns Attributable Mortality and Life Expectancy Lost in Canada: Evidence from Canadian National Nutrition Survey Linked to Routinely-Collected Health Administrative Databases. | Outcome
292 | Jiang, F, Li, Y, Xu, P, Li, J, Chen, X, Yu, H, Gao, B, Xu, B, Li, X, Chen, W. The efficacy of the Dietary Approaches to Stop Hypertension diet with respect to improving pregnancy outcomes in women with hypertensive disorders. J Hum Nutr Diet. 2019. 32:713–718. doi:10.1111/jhn.12654 | Health Status
293 | Jiang, W, Meng, X, Hou, W, Wu, X, Wang, Y, Wang, M, Chu, X, Wang, P, Sun, C, Han, T, Li, Y. Impact of overall diet quality on association between alcohol consumption and risk of hypertension: evidence from two national surveys with multiple ethnics. Eur J Clin Nutr. 2021. 75:112–122. doi:10.1038/s41430-020-00708-1 | Intervention/Exposure
294 | Jimenez-Torres, J, Alcala-Diaz, JF, Torres-Pena, JD, Gutierrez-Mariscal, FM, Leon-Acuna, A, Gomez-Luna, P, Fernandez-Gandara, C, Quintana-Navarro, GM, Fernandez-Garcia, JC, Perez-Martinez, P, Ordovas, JM, Delgado-Lista, J, Yubero-Serrano, EM, Lopez-Miranda, J. Mediterranean Diet Reduces Atherosclerosis Progression in Coronary Heart Disease: An Analysis of the CORDIOPREV Randomized Controlled Trial. Stroke. 2021. STROKEAHA120033214. doi:10.1161/STROKEAHA.120.033214 | Health Status; Outcome
295 | Jin J. Behavioral Counseling Interventions to Promote a Healthy Diet and Physical Activity to Prevent CVD in Adults Without Risk Factors. 328. | Publication Status
296 | Jin, J. Counseling on Healthy Diet and Physical Activity to Prevent Cardiovascular Disease. JAMA. 2020. 324:2114. doi:10.1001/jama.2020.22344 | Study Design; Publication Status
297 | Johansson, A, Acosta, S. Diet and Lifestyle as Risk Factors for Carotid Artery Disease: A Prospective Cohort Study. Cerebrovasc Dis. 2020. 49:563–569. doi:10.1159/000510907 | Intervention/Exposure
298 | Joyce, BT, Wu, D, Hou, L, Dai, Q, Castaneda, SF, Gallo, LC, Talavera, GA, Sotres-Alvarez, D, Van Horn, L, Beasley, JM, Khambaty, T, Elfassy, T, Zeng, D, Mattei, J, Corsino, L, Daviglus, ML. DASH diet and prevalent metabolic syndrome in the Hispanic Community Health Study/Study of Latinos. Preventive Medicine Reports. 2019. 15. doi:10.1016/j.pmedr.2019.100950 | Study Design
299 | Judiono, , Ichwanuddin, , Olifa, N, Moesiyanti, YES, Surmita, , Purba, A. Integrated nutrition interventions reduce metabolic syndrome: study of integrated interventions by diet, behavior, physical activity on overweight in junior high school children in bandung city. Annals of nutrition & metabolism. 2019. 75:388-. doi:10.1159/000501751 | Publication Status
300 | Julibert, A, Bibiloni, MDM, Bouzas, C, Martínez-González, Á M, Salas-Salvadó, J, Corella, D, Zomeño, MD, Romaguera, D, Vioque, J, Alonso-Gómez, ÁM, Wärnberg, J, Martínez, JA, Serra-Majem, L, Estruch, R, Tinahones, FJ, Lapetra, J, Pintó, X, Lopez-Miranda, J, García-Molina, L, Gaforio, JJ, Matía-Martín, P, Daimiel, L, Martín-Sánchez, V, Vidal, J, Vázquez, C, Ros, E, Toledo, E, Becerra-Tomás, N, Pórtoles, O, Pérez-Vega, KA, Fiol, M, Torres-Collado, L, Tojal-Sierra, L, Carabaño-Moral, R, Abete, I, Sanchez-Villegas, A, Casas, R, Bernal-López, MR, Santos-Lozano, JM, Galera, A, Ugarriza, L, Ruiz-Canela, M, Babio, N, Coltell, O, Schröder, H, Konieczna, J, Orozco-Beltrán, D, Sorto-Sánchez, C, Eguaras, S, Barrubés, L, Fitó, M, Tur, JA. Total and subtypes of dietary fat intake and its association with components of the metabolic syndrome in a mediterranean population at high cardiovascular risk. Nutrients. 2019. 11. doi:10.3390/nu11071493 | Study Design; Intervention/Exposure
301 | Julibert, A, Del Mar Bibiloni, M, Gallardo-Alfaro, L, Abbate, M, Martinez-Gonzalez, MA, Salas-Salvado, J, Corella, D, Fito, M, Martinez, JA, Alonso-Gomez, AM, Warnberg, J, Vioque, J, Romaguera, D, Lopez-Miranda, J, Estruch, R, Tinahones, FJ, Lapetra, J, Serra-Majem, L, Cano-Ibanez, N, Martin-Sanchez, V, Pinto, X, Gaforio, JJ, Matia-Martin, P, Vidal, J, Vazquez, C, Daimiel, L, Ros, E, Sayon-Orea, C, Becerra-Tomas, N, Gimenez-Alba, IM, Castaner, O, Abete, I, Tojal-Sierra, L, Perez-Lopez, J, Notario-Barandiaran, L, Colom, A, Garcia-Rios, A, Castro-Barquero, S, Bernal, R, Santos-Lozano, JM, Fernandez-Lazaro, CI, Hernandez-Alonso, P, Saiz, C, Zomeno, MD, Zulet, MA, Bello-Mora, MC, Basterra-Gortari, J, Canudas, S, Goday, A, Tur, JA, Predimed-Plus investigators. Metabolic Syndrome Features and Excess Weight Were Inversely Associated with Nut Consumption after 1-Year Follow-Up in the PREDIMED-Plus Study. J Nutr. 2020. 150:3161–3170. doi:10.1093/jn/nxaa289 | Intervention/Exposure
302 | Jung, SM, Haddad, EH, Kaur, A, Sirirat, R, Kim, AY, Oda, K, Rajaram, S, Sabaté, J. A Non-Probiotic Fermented Soy Product Reduces Total and LDL Cholesterol: a Randomized Controlled Crossover Trial. Nutrients. 2021. 13. doi:10.3390/nu13020535 | Intervention/Exposure
303 | Kahleova H, Berrien-Lopez R, Holtz D, Green A, Sheinberg R, Gujral H, Holubkov R, Barnard ND. Nutrition for Hospital Workers During a Crisis: Effect of a Plant-Based Dietary Intervention on Cardiometabolic Outcomes and Quality of Life in Healthcare Employees During the COVID-19 Pandemic. 16. | Intervention/Exposure
304 | Kahleova H, Rembert E, Nowak A, Holubkov R, Barnard ND. Effect of a diet intervention on cardiometabolic outcomes: Does race matter? A randomized clinical trial. 41. | Intervention/Exposure; Publication Status
305 | Kahleova, H, McCann, J, Alwarith, J, Rembert, E, Tura, A, Holubkov, R, Barnard, ND. A plant-based diet in overweight adults in a 16-week randomized clinical trial: The role of dietary acid load. Clinical Nutrition ESPEN. 2021. 44:150. | Intervention/Exposure
306 | Kahleova, H, Levin, S, Barnard, ND. Plant-Based Diets for Healthy Aging. Journal of the American College of Nutrition. 2020. 1–2. doi:10.1080/07315724.2020.1790442 | Study Design; Publication Status
307 | Kahleova, H, Petersen, KF, Shulman, GI, Alwarith, J, Rembert, E, Tura, A, Hill, M, Holubkov, R, Barnard, ND. Effect of a Low-Fat Vegan Diet on Body Weight, Insulin Sensitivity, Postprandial Metabolism, and Intramyocellular and Hepatocellular Lipid Levels in Overweight Adults: A Randomized Clinical Trial. JAMA Netw Open. 2020. 3:e2025454. doi:10.1001/jamanetworkopen.2020.25454 | Intervention/Exposure
308 | Kalkuz, S, Demircan, A. Effects of the Mediterranean diet adherence on body composition, blood parameters and quality of life in adults. Postgrad Med J. 2020. doi:10.1136/postgradmedj-2020-138667 | Study Design
309 | Kang J, Moser DK, Biddle MJ, Oh G, Lennie TA. Age- and sex-matched comparison of diet quality in patients with heart failure to similarly aged healthy older adults. 10. | Study Design
310 | Kang, Augustine, Dulin, Akilah, Risica, Patricia Markham. Relationship between adherence to diet and physical activity guidelines and self-efficacy among black women with high blood pressure. Journal of Health Psychology. 2022. 27:663–673. doi:10.1177/1359105320967105 | Study Design; Intervention/Exposure
311 | Kaplan, A, Zelicha, H, Yaskolka Meir, A, Rinott, E, Tsaban, G, Levakov, G, Prager, O, Salti, M, Yovell, Y, Ofer, J, Huhn, S, Beyer, F, Witte, V, Villringer, A, Meiran, N, Emesh, TB, Kovacs, P, Von Bergen, M, Ceglarek, U, Blüher, M, Stumvoll, M, Hu, FB, Stampfer, MJ, Friedman, A, Shelef, I, Avidan, G, Shai, I. The effect of a high-polyphenol Mediterranean diet (Green-MED) combined with physical activity on age-related brain atrophy: the Dietary Intervention Randomized Controlled Trial Polyphenols Unprocessed Study (DIRECT PLUS). American Journal of Clinical Nutrition. 2022. 115:1270. | Outcome; Data Overlap
312 | Kapoor, D, Gupta, Y, Desai, A, Praveen, D, Joshi, R, Rozati, R, Bhatla, N, Prabhakaran, D, Reddy, P, Patel, A, Tandon, N. Lifestyle intervention programme for Indian women with history of gestational diabetes mellitus. Global Health, Epidemiology and Genomics. 2019. 4. doi:10.1017/gheg.2018.18 | Country
313 | Karatzi, K, Moschonis, G, Botsi, E, Liatis, S, Tsochev, K, De Miguel-Etayo, P, Kivela, J, Wikstrom, K, Dimova, R, Antal, E, Lamiquiz-Moneo, I, Rurik, I, Cardon, G, Iotova, V, Makrilakis, K, Manios, Y, On Behalf Of The Feel Diabetes-Study, Group. Lipidemic Profile Changes over a Two-Year Intervention Period: Who Benefited Most from the Feel4Diabetes Program?. Nutrients. 2020. 12. doi:10.3390/nu12123736 | Intervention/Exposure
314 | Karbasi S, Bahrami A, Hanafi-Bojd MY, Khorasanchi Z, Zarban A, Ferns GA. Maternal Adherence to a Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern and the Relationship to Breast Milk Nutrient Content. | Study Design
315 | Karunawan, NH, Radityo, MA, Irawan, H, Poerniawan, C, Aziz, A, Affandi, M, Vera, YV, Marina, F. The effect of mobile phone-based interventions for controlling blood pressure in patients with uncontrolled hypertension grade ii. Journal of the hong kong college of cardiology. 2020. 28:76-. | Publication Status
316 | Kebbe, M, Gao, M, Perez-Cornago, A, Jebb, SA, Piernas, C. Adherence to international dietary recommendations in association with all-cause mortality and fatal and non-fatal cardiovascular disease risk: a prospective analysis of UK Biobank participants. BMC Med. 2021. 19:134. doi:10.1186/s12916-021-02011-7 | Intervention/Exposure
317 | Keenan S, Cooke MB, Chen WS, Wu S, Belski R. The Effects of Intermittent Fasting and Continuous Energy Restriction with Exercise on Cardiometabolic Biomarkers, Dietary Compliance, and Perceived Hunger and Mood: Secondary Outcomes of a Randomised, Controlled Trial. 14. | Intervention/Exposure
318 | Kelly NA, Soroka O, Onyebeke C, Pinheiro LC, Banerjee S, Safford MM, Goyal P. Association of healthy lifestyle and all-cause mortality according to medication burden. | Outcome
319 | Kenđel Jovanović, G, Mrakovcic-Sutic, I, Pavičić Žeželj, S, Benjak Horvat, I, Šuša, L, Rahelić, D, Klobučar Majanović, S. Metabolic and Hepatic Effects of Energy-Reduced Anti-Inflammatory Diet in Younger Adults with Obesity. Canadian Journal of Gastroenterology and Hepatology. 2021. 2021. doi:10.1155/2021/6649142 | Intervention/Exposure
320 | Kendel Jovanovic, G, Mrakovcic-Sutic, I, Pavicic Zezelj, S, Susa, B, Rahelic, D, Klobucar Majanovic, S. The Efficacy of an Energy-Restricted Anti-Inflammatory Diet for the Management of Obesity in Younger Adults. Nutrients. 2020. 12. doi:10.3390/nu12113583 | Study Design
321 | Keskitalo, A, Munukka, E, Aatsinki, A, Saleem, W, Kartiosuo, N, Lahti, L, Huovinen, P, Elo, LL, Pietilä, S, Rovio, SP, Niinikoski, H, Viikari, J, Rönnemaa, T, Lagström, H, Jula, A, Raitakari, O, Pahkala, K. An Infancy-Onset 20-Year Dietary Counselling Intervention and Gut Microbiota Composition in Adulthood. Nutrients. 2022. 14. | Intervention/Exposure; Outcome
322 | Khalfallah, M, Elnagar, B, Soliman, SS, Eissa, A, Allaithy, A. The Value of Intermittent Fasting and Low Carbohydrate Diet in Prediabetic Patients for the Prevention of Cardiovascular Diseases. Papel do Jejum Intermitente e da Dieta Restrita em Carboidratos na Prevenção de Doenças Cardiovasculares em Pacientes Pré-Diabéticos. 2023. 120:e20220606. | Intervention/Exposure
323 | Khalid, GT, Mohammed, ZJ. Assessment of the risk factors of pregnancy induced hypertension among pregnant women in al-basra maternity and children hospital. Journal of Cardiovascular Disease Research. 2021. 12:159. | Study Design; Intervention/Exposure
324 | Khan, I, Kwon, M, Shivappa, N, Hebert J R, Kim, MK. Proinflammatory Dietary Intake is Associated with Increased Risk of Metabolic Syndrome and Its Components: Results from the Population-Based Prospective Study. Nutrients. 2020. 12. doi:10.3390/nu12041196 | Intervention/Exposure
325 | Killeen SL, Phillips CM, Delahunt A, Yelverton CA, Shivappa N, Hébert JR, Kennelly MA, Cronin M, Mehegan J, McAuliffe FM. Effect of an Antenatal Lifestyle Intervention on Dietary Inflammatory Index and Its Associations with Maternal and Fetal Outcomes: A Secondary Analysis of the PEARS Trial. 13. | Intervention/Exposure
326 | Kim H, Appel LJ, Lichtenstein AH, Wong KE, Chatterjee N, Rhee EP, Rebholz CM. Metabolomic Profiles Associated With Blood Pressure Reduction in Response to the DASH and DASH-Sodium Dietary Interventions. | Study Duration; Outcome
327 | Kim H, Lichtenstein AH, White K, Wong KE, Miller ER 3rd, Coresh J, Appel LJ, Rebholz CM. Plasma Metabolites Associated with a Protein-Rich Dietary Pattern: Results from the OmniHeart Trial. 66. | Intervention/Exposure; Study Duration
328 | Kim Y, Kim YM, Shin MH, Koh SB, Chang Kim H, Kim MK. Empirically identified dietary patterns and metabolic syndrome risk in a prospective cohort study: The Cardiovascular Disease Association Study. 41. | Outcome
329 | Kim, H, Yu, B, Li, X, Wong, KE, Boerwinkle, E, Seidelmann, SB, Levey, AS, Rhee, EP, Coresh, J, Rebholz, CM. Serum metabolomic signatures of plant-based diets and incident chronic kidney disease. American Journal of Clinical Nutrition. 2022. 116:151. | Outcome
330 | Kim, H, Lee, K, Rebholz, CM, Kim, J. Association between unhealthy plant-based diets and the metabolic syndrome in adult men and women: A population-based study in South Korea. British Journal of Nutrition. 2021. 125:577–590. doi:10.1017/S0007114520002895 | Study Design
331 | Kim, H, Lichtenstein, AH, Wong, KE, Appel, LJ, Coresh, J, Rebholz, CM. Urine Metabolites Associated with the Dietary Approaches to Stop Hypertension (DASH) Diet: Results from the DASH-Sodium Trial. Mol Nutr Food Res. 2021. 65:e2000695. doi:10.1002/mnfr.202000695 | Study Duration
332 | Kim, MJ, Lim, H-S, Lee, H-H, Kim, T-H, Park, Y. Dietary assessment, nutrition knowledge, and pregnancy outcome in high-risk pregnant Korean women. Clinical and Experimental Obstetrics and Gynecology. 2021. 48:1178. | Comparator
333 | Kinnear, FJ, Lithander, FE, Searle, A, Bayly, G, Wei, C, Stensel, DJ, Thackray, AE, Hunt, L, Shield, JPH. Reducing cardiovascular disease risk among families with familial hypercholesterolaemia by improving diet and physical activity: a randomised controlled feasibility trial. BMJ Open. 2020. 10:e044200. doi:10.1136/bmjopen-2020-044200 | Intervention/Exposure
334 | Kishida R, Yamagishi K, Maruyama K, Okada C, Tanaka M, Ikeda A, Hayama-Terada M, Shimizu Y, Muraki I, Umesawa M, Imano H, Brunner EJ, Sankai T, Okada T, Kitamura A, Kiyama M, Iso H. Dietary intake of beans and risk of disabling dementia: The Circulatory Risk in Communities Study (CIRCS). | Intervention/Exposure
335 | Klonizakis, M, Grammatikopoulou, MG, Theodoridis, X, Milner, M, Liu, Y, Chourdakis, M. Effects of long-versus short-term exposure to the mediterranean diet on skin microvascular function and quality of life of healthy adults in Greece and the UK. Nutrients. 2019. 11. doi:10.3390/nu11102487 | Study Duration
336 | Knight R, Cedillo Y, Judd S, Tison S, Baker E, Moellering D. Dietary inflammation score is associated with perceived stress, depression, and cardiometabolic health risk factors among a young adult cohort of women. 51. | Study Design
337 | Kobayashi, M, Sasazuki, S, Shimazu, T, Sawada, N, Yamaji, T, Iwasaki, M, Mizoue, T, Tsugane, S. Association of dietary diversity with total mortality and major causes of mortality in the Japanese population: JPHC study. Eur J Clin Nutr. 2020. 74:54–66. doi:10.1038/s41430-019-0416-y | Intervention/Exposure
338 | Koeder, C, Alzughayyar, D, Anand, C, Kranz, R-M, Husain, S, Schoch, N, Hahn, A, Englert, H. The healthful plant-based diet index as a tool for obesity prevention—The healthy lifestyle community program cohort 3 study. Obesity Science and Practice. 2022. | Study Design
339 | Koeder, C, Hahn, A, Englert, H. Effect of a 6-Month Controlled Lifestyle Intervention on Common Carotid Intima-Media Thickness. J Nutr Health Aging. 2021. 25:869–877. doi:10.1007/s12603-021-1628-0 | Intervention/Exposure
340 | Koemel NA, Senior AM, Celermajer DS, Grech A, Gill TP, Simpson SJ, Raubenheimer D, Skilton MR. Multi-Nutrient Analysis of Dietary Macronutrients with All-Cause, Cardiovascular, and Cancer Mortality: Data from NHANES 1999–2014. 15. | Intervention/Exposure
341 | Kohli A, Pandey RM, Siddhu A, Reddy KS. Development of a diet pattern assessment tool for coronary heart disease risk reduction. 4. | Outcome; Country
342 | Kondo K, Miura K, Okamura T, Okayama A, Ueshima H. Dietary Factors, Dietary Patterns, and Cardiovascular Disease Risk in Representative Japanese Cohorts: NIPPON DATA80/90. | Study Design
343 | Kondo, K, Miura, K, Tanaka-Mizuno, S, Kadota, A, Arima, H, Okuda, N, Fujiyoshi, A, Miyagawa, N, Yoshita, K, Okamura, T, Okayama, A, Ueshima, H. Cardiovascular risk assessment chart by dietary factors in Japan: NIPPON DATA80. Circulation Journal. 2019. 83:1254–1260. doi:10.1253/circj.CJ-18-1002 | Intervention/Exposure
344 | Kou M, Li X, Shao X, Grundberg E, Wang X, Ma H, Heianza Y, Alfredo Martinez J, Bray GA, Sacks FM, Qi L. DNA Methylation of Birthweight-Blood Pressure Genes and Changes of Blood Pressure in Response to Weight-Loss Diets in the POUNDS Lost Trial. | Intervention/Exposure
345 | Kouvari, M, Boutari, C, Chrysohoou, C, Fragkopoulou, E, Antonopoulou, S, Tousoulis, D, Pitsavos, C, Panagiotakos, DB, Mantzoros, CS, Attica study Investigators. Mediterranean diet is inversely associated with steatosis and fibrosis and decreases ten-year diabetes and cardiovascular risk in NAFLD subjects: Results from the ATTICA prospective cohort study. Clin Nutr. 2021. 40:3314–3324. doi:10.1016/j.clnu.2020.10.058 | Outcome
346 | Kouvari, M, Tsiampalis, T, Chrysohoou, C, Georgousopoulou, E, Notara, V, Souliotis, K, Psaltopoulou, T, Yannakoulia, M, Pitsavos, C, Panagiotakos, DB. A Mediterranean diet microsimulation modeling in relation to cardiovascular disease burden: the ATTICA and GREECS epidemiological studies. Eur J Clin Nutr. 2021. doi:10.1038/s41430-021-00967-6 | Study Design
347 | Krishnan S, Gertz ER, Adams SH, Newman JW, Pedersen TL, Keim NL, Bennett BJ. Effects of a diet based on the Dietary Guidelines on vascular health and TMAO in women with cardiometabolic risk factors. | Outcome
348 | Krishnan, S, O’Connor, LE, Wang, Y, Gertz, ER, Campbell, WW, Bennett, BJ. Adopting a Mediterranean-style eating pattern with low, but not moderate, unprocessed, lean red meat intake reduces fasting serum trimethylamine N-oxide (TMAO) in adults who are overweight or obese. British Journal of Nutrition. 2022. 128:1738. | Outcome
349 | Kunduraci, YE, Ozbek, H. Does the Energy Restriction Intermittent Fasting Diet Alleviate Metabolic Syndrome Biomarkers? A Randomized Controlled Trial. Nutrients. 2020. 12. doi:10.3390/nu12103213 | Intervention/Exposure
350 | Kuyumcu, A, Kuyumcu, MS. Mediterranean diet and DASH diet can be protective for ascending aortic aneurysm. Anatolian journal of cardiology. 2020. 24:98–99. | Study Design; Publication Status
351 | Kvist, K, Laursen, ASD, Overvad, K, Jakobsen, MU. Substitution of Milk with Whole-Fat Yogurt Products or Cheese Is Associated with a Lower Risk of Myocardial Infarction: The Danish Diet, Cancer and Health cohort. J Nutr. 2020. 150:1252–1258. doi:10.1093/jn/nxz337 | Intervention/Exposure
352 | Kwaśniewska M, Pikala M, Grygorczuk O, Waśkiewicz A, Stepaniak U, Pająk A, Kozakiewicz K, Nadrowski P, Zdrojewski T, Puch-Walczak A, Tykarski A, Drygas W. Dietary Antioxidants, Quality of Nutrition and Cardiovascular Characteristics among Omnivores, Flexitarians and Vegetarians in Poland-The Results of Multicenter National Representative Survey WOBASZ. 12. | Study Design; Intervention/Exposure
353 | Kwiatkowska I, Olszak J, Brożek A, Blacha A, Nowicki M, Maćkowiak K, Formanowicz P, Formanowicz D. Is It Feasible to Predict Cardiovascular Risk among Healthy Vegans, Lacto-/Ovo-Vegetarians, Pescatarians, and Omnivores under Forty?. 20. | Study Design; Intervention/Exposure
354 | Lafrenière, J, Carbonneau, E, Laramée, C, Corneau, C, Robitaille, J, Labonté, ME, Lamarche, B, Lemieux, S. Is the Canadian healthy eating index 2007 an appropriate diet indicator of metabolic health? insights from dietary pattern analysis in the PREDISE study. Nutrients. 2019. 11. doi:10.3390/nu11071597 | Study Design
355 | Lagstrom, H, Stenholm, S, Akbaraly, T, Pentti, J, Vahtera, J, Kivimaki, M, Head, J. Diet quality as a predictor of cardiometabolic disease-free life expectancy: the Whitehall II cohort study. Am J Clin Nutr. 2020. 111:787–794. doi:10.1093/ajcn/nqz329 | Outcome
356 | Laitinen, TomiT, Nuotio, Joel, Rovio, SuviP, Niinikoski, Harri, Juonala, Markus, Magnussen, CostanG, Jokinen, Eero, Lagström, Hanna, Jula, Antti, Viikari, JormaSA, Rönnemaa, Tapani, Simell, Olli, Raitakari, OlliT, Pahkala, Katja. Dietary Fats and Atherosclerosis From Childhood to Adulthood. Pediatrics. 2020. 145:1–9. doi:10.1542/peds.2019-2786 | Intervention/Exposure
357 | Laitinen, TT, Nuotio, J, Niinikoski, H, Juonala, M, Rovio, SP, Viikari, JSA, Ronnemaa, T, Magnussen, CG, Sabin, M, Burgner, D, Jokinen, E, Lagstrom, H, Jula, A, Simell, O, Raitakari, OT, Pahkala, K. Attainment of Targets of the 20-Year Infancy-Onset Dietary Intervention and Blood Pressure Across Childhood and Young Adulthood: The Special Turku Coronary Risk Factor Intervention Project (STRIP). Hypertension. 2020. 76:1572–1579. doi:10.1161/HYPERTENSIONAHA.120.15075 | Intervention/Exposure
358 | Lampure, A, Adriouch, S, Castetbon, K, Deglaire, A, Schlich, P, Peneau, S, Fezeu, L, Hercberg, S, Mejean, C. Relationship between sensory liking for fat, sweet or salt and cardiometabolic diseases: mediating effects of diet and weight status. Eur J Nutr. 2020. 59:249–261. doi:10.1007/s00394-019-01904-x | Intervention/Exposure
359 | Lang X, Liu Z, Islam S, Han G, Rangarajan S, Tse LA, Mushtaha M, Wang J, Hu L, Qiang D, Zhu Y, Yusuf S, Lin Y, Hu B, On Behalf Of The Pure-China Investigators. Interaction of Depression and Unhealthy Diets on the Risk of Cardiovascular Diseases and All-Cause Mortality in the Chinese Population: A PURE Cohort Substudy. 14. | Intervention/Exposure; Country
360 | Laouali N, Benmarhnia T, Oulhote Y. Potential benefits of joint hypothetical interventions on diet, lead, and cadmium on mortality in US adults. 21. | Intervention/Exposure
361 | Larsson, SC, Wolk, A, Bäck, M. Dietary patterns, food groups, and incidence of aortic valve stenosis: A prospective cohort study. International Journal of Cardiology. 2019. 283:184–188. doi:10.1016/j.ijcard.2018.11.007 | Outcome
362 | Latorre-Millan, M, Ruperez, AI, Gonzalez-Gil, EM, Santaliestra-Pasias, A, Vazquez-Cobela, R, Gil-Campos, M, Aguilera, CM, Gil, A, Moreno, LA, Leis, R, Bueno, G. Dietary Patterns and Their Association with Body Composition and Cardiometabolic Markers in Children and Adolescents: Genobox Cohort. Nutrients. 2020. 12. doi:10.3390/nu12113424 | Study Design
363 | Laursen, AnneSofieD, Thomsen, AnneL, Beck, Anne, Overvad, Kim, Jakobsen, MarianneU. Theoretical substitutions between dairy products and all-cause and cause-specific mortality. Results from the Danish diet, cancer and health cohort. British Journal of Nutrition. 2022. 127:1557–1566. doi:10.1017/S0007114521002464 | Study Design; Intervention/Exposure
364 | Lavie, M, Lavie, I, Maslovitz, S. Paleolithic diet during pregnancy-A potential beneficial effect on metabolic indices and birth weight. Eur J Obstet Gynecol Reprod Biol. 2019. 242:7–11. doi:10.1016/j.ejogrb.2019.08.013 | Study Design
365 | Lazarova SV, Sutherland JM, Jessri M. Adherence to emerging plant-based dietary patterns and its association with cardiovascular disease risk in a nationally representative sample of Canadian adults. | Study Design
366 | Lee C, Yang Q, Wolever RQ, Vorderstrasse A. Health Behavior Trajectories in High Cardiovascular Risk Populations: Secondary Analysis of a Clinical Trial. 36. | Intervention/Exposure
367 | Lee E, Kim JM. The association of the Korean Healthy Eating Index with chronic conditions in middle-aged single-person households. 17. | Study Design
368 | Lee J, Hoang T, Lee S, Kim J. Association Between Dietary Patterns and Dyslipidemia in Korean Women. 8. | Study Design
369 | Lee, Y-N, Kang, P. Relationship between the 10-Year Risk for Atherosclerotic Cardiovascular Disease and the Dietary Inflammatory Index among Korean Adults Based on the Seventh Korea National Health and Nutrition Examination Survey (KNHANES). BioMed Research International. 2020. 2020. | Study Design
370 | Lee, YQ, Colega, M, Sugianto, R, Lai, JS, Godfrey, KM, Tan, KH, Shek, LP-C, Loy, SL, Müller-Riemenschneider, F, Padmapriya, N, Chong, YS, Eriksson, JG, Chan, JKY, Chan, S-Y, Tai, BC, Chong, MF-F. Tracking of dietary patterns between pregnancy and 6 years post-pregnancy in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) study. European Journal of Nutrition. 2022. 61:985. | Outcome; Comparator
371 | Lee-Bravatti MA, O’Neill HJ, Wurth RC, Sotos-Prieto M, Gao X, Falcon LM, Tucker KL, Mattei J. Lifestyle Behavioral Factors and Integrative Successful Aging Among Puerto Ricans Living in the Mainland United States. 76. | Outcome
372 | Lehtovirta, M, Matthews, LA, Laitinen, TT, Nuotio, J, Niinikoski, H, Rovio, SP, Lagstrom, H, Viikari, JSA, Ronnemaa, T, Jula, A, Ala-Korpela, M, Raitakari, OT, Pahkala, K. Achievement of the Targets of the 20-Year Infancy-Onset Dietary Intervention-Association with Metabolic Profile from Childhood to Adulthood. Nutrients. 2021. 13. doi:10.3390/nu13020533 | Intervention/Exposure
373 | Lennerz BS, Mey JT, Henn OH, Ludwig DS. Behavioral Characteristics and Self-Reported Health Status among 2029 Adults Consuming a “Carnivore Diet”. 5. | Study Design
374 | Leskinen, HM, Tringham, M, Karjalainen, H, Iso-Touru, TK, Hietaranta-Luoma, HL, Marnila, PJ, Pihlava, JM, Hurme, T, Kankaanpaa, SJ, Puolijoki, H, Akerman, K, Tanner, L, Sandell, M, Vahakangas, K, Hopia, A, Tahvonen, R, Rokka, LS. APOE Genotype Disclosure and Lifestyle Advice in a Randomized Intervention Study with Finnish Participants. J Nutr. 2021. 151:85–97. doi:10.1093/jn/nxaa316 | Intervention/Exposure
375 | Leu, HB, Chung, CM, Chen, JW, Pan, WH. The Mediterranean diet reduces the genetic risk of chromosome 9p21 for myocardial infarction in an Asian population community cohort. Sci Rep. 2019. 9:18405. doi:10.1038/s41598-019-54938-w | Intervention/Exposure; Country
376 | Leyva, F, Guerrero, E, Arcila, D, Serralde, A, Flores, A, García, M, Gulías, A, Sutherland, M, Castillo-Martínez, L. Association between stages of change regarding weight reduction in patients with cardiovascular risk factors: A randomized controlled trial. Asociación entre las etapas de cambio con la reducción de peso en pacientes con factores de riesgo cardiovascular: Ensayo clínico controlado. 2021. 48:381. | Outcome; Comparator
377 | Li S, Liu Z, Joseph P, Hu B, Yin L, Tse LA, Rangarajan S, Wang C, Wang Y, Islam S, Liu W, Lu F, Li Y, Hou Y, Qiang D, Zhao Q, Li N, Lei R, Chen D, Han A, Liu G, Zhang P, Zhi Y, Liu C, Yang J, Resalaiti A, Ma H, Ma Y, Liu Y, Xing X, Xiang Q, Liu Z, Sheng Y, Tang J, Liu L, Yusuf S, Li W. Modifiable risk factors associated with cardiovascular disease and mortality in China: a PURE substudy. | Country
378 | Li, J, Guasch-Ferre, M, Chung, W, Ruiz-Canela, M, Toledo, E, Corella, D, Bhupathiraju, SN, Tobias, DK, Tabung, FK, Hu, J, Zhao, T, Turman, C, Feng, YA, Clish, CB, Mucci, L, Eliassen, AH, Costenbader, KH, Karlson, EW, Wolpin, BM, Ascherio, A, Rimm, EB, Manson, JE, Qi, L, Martinez-Gonzalez, MA, Salas-Salvado, J, Hu, FB, Liang, L. The Mediterranean diet, plasma metabolome, and cardiovascular disease risk. Eur Heart J. 2020. 41:2645–2656. doi:10.1093/eurheartj/ehaa209 | Comparator
379 | Li, L, Shan, Z, Wan, Z, Li, R, Geng, T, Lu, Q, Zhu, K, Qiu, Z, Zhang, X, Liu, Y, Liu, L, Pan, A, Liu, G. Associations of lower-carbohydrate and lower-fat diets with mortality among people with prediabetes. The American journal of clinical nutrition. 2022. | Intervention/Exposure
380 | Li, M, Shi, Z. Ultra-Processed Food Consumption Associated with Incident Hypertension among Chinese Adults—Results from China Health and Nutrition Survey 1997–2015. Nutrients. 2022. 14. | Country
381 | Li, Q, Liu, C, Zhang, S, Li, R, Zhang, Y, He, P, Zhang, Z, Liu, M, Zhou, C, Ye, Z, Wu, Q, Li, H, Qin, X. Dietary carbohydrate intake and new-onset hypertension: A nationwide cohort study in China. Hypertension. 2021. 422–430. doi:10.1161/HYPERTENSIONAHA.120.16751 | Intervention/Exposure
382 | Li, S, Lin, G, Chen, J, Chen, Z, Xu, F, Zhu, F, Zhang, J, Yuan, S. The effect of periodic ketogenic diet on newly diagnosed overweight or obese patients with type 2 diabetes. BMC endocrine disorders. 2022. 22:34. | Health Status
383 | Li, Y, Wang, DD, Satija, A, Ivey, KL, Li, J, Wilkinson, JE, Li, R, Baden, M, Chan, AT, Huttenhower, C, Rimm, EB, Hu, FB, Sun, Q. Plant-Based Diet Index and Metabolic Risk in Men: Exploring the Role of the Gut Microbiome. Journal of Nutrition. 2021. 151:2780. | Study Design
384 | Li, Y, Schoufour, J, Wang, DD, Dhana, K, Pan, A, Liu, X, Song, M, Liu, G, Shin, HJ, Sun, Q, Al-Shaar, L, Wang, M, Rimm, EB, Hertzmark, E, Stampfer, MJ, Willett, WC, Franco, OH, Hu, FB. Healthy lifestyle and life expectancy free of cancer, cardiovascular disease, and type 2 diabetes: prospective cohort study. BMJ. 2020. 368:l6669. doi:10.1136/bmj.l6669 | Intervention/Exposure; Outcome
385 | Li, Z, Heber, D. The Pritikin Diet. JAMA. 2020. 323:1104. doi:10.1001/jama.2019.21266 | Study Design; Publication Status
386 | Liang, Jie, Zhao, Jun-Kang, Wang, Ju-Ping, Wang, Tong. Association between animal source foods consumption and risk of hypertension: a cohort study. European Journal of Nutrition. 2021. 60:2469–2483. doi:10.1007/s00394-020-02423-w | Intervention/Exposure
387 | Liese, AD, Couch, SC, The, NS, Crandell, JL, Lawrence, JM, Crume, TL, Mayer-Davis, EJ, Zhong, VW, Urbina, EM. Association between diet quality indices and arterial stiffness in youth with type 1 diabetes: SEARCH for Diabetes in Youth Nutrition Ancillary Study. J Diabetes Complications. 2020. 34:107709. doi:10.1016/j.jdiacomp.2020.107709 | Health Status
388 | Lim GB. Mediterranean diet superior to low-fat diet for secondary prevention of CVD. 19. | Publication Status
389 | Lim, CC, Hayes, RB, Ahn, J, Shao, Y, Silverman, DT, Jones, RR, Thurston, GD. Mediterranean Diet and the Association between Air Pollution and Cardiovascular Disease Mortality Risk. Circulation. 2019. 139:1766–1775. doi:10.1161/CIRCULATIONAHA.118.035742 | Intervention/Exposure; Comparator
390 | Lim, CGY, Tai, ES, van Dam, RM. Replacing dietary carbohydrates and refined grains with different alternatives and risk of cardiovascular diseases in a multi-ethnic Asian population. The American journal of clinical nutrition. 2022. | Intervention/Exposure
391 | Lim, SX, Cox, V, Rodrigues, N, Colega, MT, Barton, SJ, Childs, CE, Conlon, CA, Wall, CR, Cutfield, WS, Chan, S-Y, Godfrey, KM, Chong, MF-F. Evaluation of Preconception Dietary Patterns in Women Enrolled in a Multisite Study. Current Developments in Nutrition. 2022. 6. | Study Design; Outcome
392 | Lingfors, H, Persson, LG. All-cause mortality among young men 24–26 years after a lifestyle health dialogue in a Swedish primary care setting: A longitudinal follow-up register study. BMJ Open. 2019. 9. doi:10.1136/bmjopen-2018-022474 | Intervention/Exposure; Outcome
393 | Lisón, JF, Palomar, G, Mensorio, MS, Banõs, RM, Cebolla-Martí, A, Botella, C, Benavent-Caballer, V, Rodilla, E. Impact of a Web-Based Exercise and Nutritional Education Intervention in Patients Who Are Obese with Hypertension: Randomized Wait-List Controlled Trial. Journal of Medical Internet Research. 2020. 22. doi:10.2196/14196 | Intervention/Exposure
394 | Liu L, Yang Y, Zhao Y, Zhang T. Burden of stroke and its risk factors in Yunnan province of China, 1990–2017. | Intervention/Exposure
395 | Liu, J, Zhang, Y, Lavie, CJ, Tabung, FK, Xu, J, Hu, Q, He, L, Zhang, Y. Associations of C-reactive protein and fibrinogen with mortality from all-causes, cardiovascular disease and cancer among U.S. adults. Prev Med. 2020. 139:106044. doi:10.1016/j.ypmed.2020.106044 | Intervention/Exposure
396 | Liu, Q, Wen, Q, Lv, J, Shi, Z, Guo, Y, Pei, P, Du, H, Yang, L, Chen, Y, Zhang, X, Schmidt, D, Sansome, S, Chen, J, Yu, C, Chen, Z, Li, L. The Prospective Associations of Lipid Metabolism-Related Dietary Patterns with the Risk of Diabetes in Chinese Adults. Nutrients. 2022. 14. | Outcome; Country
397 | Liu, Weida, Hu, Bo, Dehghan, Mahshid, Mente, Andrew, Wang, Chuangshi, Yan, Ruohua, Rangarajan, Sumathy, Tse, Lap Ah, Yusuf, Salim, Liu, Xiaoyun, Wang, Yang, Qiang, Deren, Hu, Lihua, Han, Aiying, Tang, Xincheng, Liu, Lisheng, Li, Wei. Fruit, vegetable, and legume intake and the risk of all-cause, cardiovascular, and cancer mortality: A prospective study. Clinical Nutrition. 2021. 40:4316–4323. doi:10.1016/j.clnu.2021.01.016 | Intervention/Exposure; Country
398 | Liu, Y, Sun, P, Shuai, P, Qiao, Q, Li, T. Fat-restricted low-glycemic index diet controls weight and improves blood lipid profile: A pilot study among overweight and obese adults in Southwest China. Medicine (Baltimore). 2021. 100:e26107. doi:10.1097/MD.0000000000026107 | Study Design
399 | Livingstone, KM, Abbott, G, Ward, J, Bowe, SJ. Unhealthy lifestyle, genetics and risk of cardiovascular disease and mortality in 76,958 individuals from the UK biobank cohort study. Nutrients. 2021. 13. | Comparator
400 | Llanaj, E, Vincze, F, Kosa, Z, Bardos, H, Dioszegi, J, Sandor, J, Adany, R. Deteriorated Dietary Patterns with Regards to Health and Environmental Sustainability among Hungarian Roma Are Not Differentiated from Those of the General Population. Nutrients. 2021. 13. doi:10.3390/nu13030721 | Study Design
401 | Lo BK, Graham ML, Folta SC, Strogatz D, Parry SA, Seguin-Fowler RA. Physical activity and healthy eating behavior changes among rural women: an exploratory mediation analysis of a randomized multilevel intervention trial. 11. | Intervention/Exposure; Outcome
402 | Lo, K, Glenn, AJ, Yeung, S, Kendall, CWC, Sievenpiper, JL, Jenkins, DJA, Woo, J. Prospective association of the portfolio diet with all-cause and cause-specific mortality risk in the mr. OS and ms. OS study. Nutrients. 2021. 13. | Intervention/Exposure
403 | Lockard B, Mardock M, Oliver JM, Byrd M, Simbo S, Jagim AR, Kresta J, Baetge CC, Jung YP, Koozehchian MS, Khanna D, Rasmussen C, Kreider RB. Comparison of Two Diet and Exercise Approaches on Weight Loss and Health Outcomes in Obese Women. 19. | Intervention/Exposure; Study Duration
404 | López-Contreras, IN, Vilchis-Gil, J, Klünder-Klünder, M, Villalpando-Carrión, S, Flores-Huerta, S. Dietary habits and metabolic response improve in obese children whose mothers received an intervention to promote healthy eating: randomized clinical trial. BMC public health. 2020. 20:1240. doi:10.1186/s12889-020-09339-4 | Intervention/Exposure
405 | Lopez-Jaramillo P, Joseph P, Lopez-Lopez JP, Lanas F, Avezum A, Diaz R, Camacho PA, Seron P, Oliveira G, Orlandini A, Rangarajan S, Islam S, Yusuf S. Risk factors, cardiovascular disease, and mortality in South America: a PURE substudy. | Intervention/Exposure
406 | López-Jaramillo P, López-López JP. Cardiovascular risk factors and death in South America. | Publication Language
407 | Lu Q, Chen J, Li R, Wang Y, Tu Z, Geng T, Liu L, Pan A, Liu G. Healthy lifestyle, plasma metabolites, and risk of cardiovascular disease among individuals with diabetes. | Health Status
408 | Lüscher, TF. Nutrition, obesity, diabetes, and cardiovascular outcomes: A deadly association. European Heart Journal. 2020. 41:2603–2607. doi:10.1093/eurheartj/ehaa622 | Study Design; Publication Status
409 | Lynch, E, Emery-Tiburcio, E, Dugan, S, White, FS, Thomason, C, Jenkins, L, Feit, C, Avery-Mamer, E, Wang, Y, Mack, L, Ragland, A. Results of ALIVE: A Faith-Based Pilot Intervention to Improve Diet Among African American Church Members. Progress in community health partnerships : research, education, and action. 2019. 13:19–30. doi:10.1353/cpr.2019.0005 | Study Design
410 | Ma J, Zeng F, Guan Q, Han L. Educational level differences in the primary and secondary prevention of stroke. | Study Design; Intervention/Exposure; Country
411 | Ma, J, Rebholz, CM, Braun, KVE, Reynolds, LM, Aslibekyan, S, Xia, R, Biligowda, NG, Huan, T, Liu, C, Mendelson, MM, Joehanes, R, Hu, EA, Vitolins, MZ, Wood, AC, Lohman, K, Ochoa-Rosales, C, van Meurs, J, Uitterlinden, A, Liu, Y, Elhadad, MA, Heier, M, Waldenberger, M, Peters, A, Colicino, E, Whitsel, EA, Baldassari, A, Gharib, SA, Sotoodehnia, N, Brody, JA, Sitlani, CM, Tanaka, T, Hill, WD, Corley, J, Deary, IJ, Zhang, Y, Schottker, B, Brenner, H, Walker, ME, Ye, S, Nguyen, S, Pankow, J, Demerath, EW, Zheng, Y, Hou, L, Liang, L, Lichtenstein, AH, Hu, FB, Fornage, M, Voortman, T, Levy, D. Whole Blood DNA Methylation Signatures of Diet Are Associated With Cardiovascular Disease Risk Factors and All-Cause Mortality. Circ Genom Precis Med. 2020. 13:e002766. doi:10.1161/CIRCGEN.119.002766 | Intervention/Exposure; Outcome
412 | Ma, Y, Sun, Y, Sun, L, Liu, X, Zeng, R, Lin, X, Li, Y. Effects of gut microbiota and fatty acid metabolism on dyslipidemia following weight-loss diets in women: Results from a randomized controlled trial. Clinical Nutrition. 2021. 40:5511. | Intervention/Exposure
413 | MacDonald CJ, Madkia AL, Mounier-Vehier C, Severi G, Boutron-Ruault MC. Associations between saturated fat intake and other dietary macronutrients and incident hypertension in a prospective study of French women. | Intervention/Exposure
414 | Macias, S, Kirma, J, Yilmaz, A, Moore, SE, McKinley, MC, McKeown, PP, Woodside, JV, Graham, SF, Green, BD. Application of 1H-NMR Metabolomics for the Discovery of Blood Plasma Biomarkers of a Mediterranean Diet. Metabolites. 2019. 9. doi:10.3390/metabo9100201 | Study Design; Outcome
415 | Maddison, R, Hargreaves, EA, Jiang, Y, Calder, AJ, Wyke, S, Gray, CM, Hunt, K, Lubans, DR, Eyles, H, Draper, N, Heke, I, Kara, S, Sundborn, G, Arandjus, C, Gao, L, Lee, P, Lim, M, Marsh, S. Rugby Fans in Training New Zealand (RUFIT NZ): a randomized controlled trial to assess the effectiveness of a healthy lifestyle program for overweight men delivered through professional rugby clubs. The international journal of behavioral nutrition and physical activity. 2023. 20:37. | Intervention/Exposure
416 | Madlala SS, Hill J, Kunneke E, Kengne AP, Peer N, Faber M. Dietary Diversity and its Association with Nutritional Status, Cardiometabolic Risk Factors and Food Choices of Adults at Risk for Type 2 Diabetes Mellitus in Cape Town, South Africa. 14. | Study Design
417 | Magriplis, E, Panagiotakos, D, Mitsopoulou, AV, Karageorgou, D, Bakogianni, I, Dimakopoulos, I, Micha, R, Michas, G, Chourdakis, M, Chrousos, GP, Roma, E, Zampelas, A. Prevalence of hyperlipidaemia in adults and its relation to the Mediterranean diet: the Hellenic National Nutrition and Health Survey (HNNHS). Eur J Prev Cardiol. 2019. 26:1957–1967. doi:10.1177/2047487319866023 | Study Design
418 | Mahjoub, F, Ben Jemaa, H, Ben Sabeh, F, Ben Amor, N, Gamoudi, A, Jamoussi, H. Impact of nutrients and Mediterranean diet on the occurrence of gestational diabetes. Libyan Journal of Medicine. 2021. 16. doi:10.1080/19932820.2021.1930346 | Study Design; Outcome
419 | Maki, KC, Wilcox, ML, Dicklin, MR, Buggia, M, Palacios, OM, Maki, CE, Kramer, M. Substituting Lean Beef for Carbohydrate in a Healthy Dietary Pattern Does Not Adversely Affect the Cardiometabolic Risk Factor Profile in Men and Women at Risk for Type 2 Diabetes. J Nutr. 2020. 150:1824–1833. doi:10.1093/jn/nxaa116 | Study Duration
420 | Malinowska AM. Easy Diet Screener: A quick and easy tool for determining dietary patterns associated with lipid profile and body adiposity. | Study Design; Intervention/Exposure
421 | Manoogian, ENC, Chaix, A, Panda, S. When to Eat: The Importance of Eating Patterns in Health and Disease. J Biol Rhythms. 2019. 34:579–581. doi:10.1177/0748730419892105 | Study Design; Intervention/Exposure; Publication Status
422 | Margerison, C, Riddell, LJ, McNaughton, SA, Nowson, CA. Associations between dietary patterns and blood pressure in a sample of Australian adults. Nutr J. 2020. 19:5. doi:10.1186/s12937-019-0519-2 | Study Design
423 | Martíncrespo-Blanco, MC, Varillas-Delgado, D, Blanco-Abril, S, Cid-Exposito, MG, Robledo-Martín, J. Effectiveness of an Intervention Programme on Adherence to the Mediterranean Diet in a Preschool Child: A Randomised Controlled Trial. Nutrients. 2022. 14. | Outcome
424 | Martinez-Gonzalez, MA, Fernandez-Lazaro, CI, Toledo, E, Diaz-Lopez, A, Corella, D, Goday, A, Romaguera, D, Vioque, J, Alonso-Gomez, AM, Warnberg, J, Martinez, JA, Serra-Majem, L, Estruch, R, Tinahones, FJ, Lapetra, J, Pinto, X, Tur, JA, Lopez-Miranda, J, Cano-Ibanez, N, Delgado-Rodriguez, M, Matia-Martin, P, Daimiel, L, Sanchez, VM, Vidal, J, Vazquez, C, Ros, E, Buil-Cosiales, P, Portoles, O, Soria-Florido, M, Konieczna, J, Navarrete-Munoz, EM, Tojal-Sierra, L, Fernandez-Garcia, JC, Abete, I, Henriquez-Sanchez, P, Munoz-Garach, A, Santos-Lozano, JM, Corbella, E, Bibiloni, MDM, Becerra-Tomas, N, Barragan, R, Castaner, O, Fiol, M, Garcia de la Hera, M, Bello-Mora, MC, Gea, A, Babio, N, Fito, M, Ruiz-Canela, M, Zazpe, I, Salas-Salvado, J. Carbohydrate quality changes and concurrent changes in cardiovascular risk factors: a longitudinal analysis in the PREDIMED-Plus randomized trial. Am J Clin Nutr. 2020. 111:291–306. doi:10.1093/ajcn/nqz298 | Intervention/Exposure; Comparator
425 | Martinez-Perez, C, San-Cristobal, R, Guallar-Castillon, P, Martínez-González, MÁ, Salas-Salvadó, J, Corella, D, Castañer, O, Martinez, JA, Alonso-Gómez, ÁM, Wärnberg, J, Vioque, J, Romaguera, D, López-Miranda, J, Estruch, R, Tinahones, FJ, Lapetra, J, Serra-Majem, L, Bueno-Cavanillas, A, Tur, JA, Sánchez, VM, Pintó, X, Gaforio, JJ, Matía-Martín, P, Vidal, J, Vázquez, C, Ros, E, Bes-Rastrollo, M, Babio, N, Sorlí, JV, Lassale, C, Pérez-Sanz, B, Vaquero-Luna, J, Bazán, MJA, Barceló-Iglesias, MC, Konieczna, J, Ríos, AG, Bernal-López, MR, Santos-Lozano, JM, Toledo, E, Becerra-Tomás, N, Portoles, O, Zomeño, MD, Abete, I, Moreno-Rodriguez, A, Lecea-Juarez, O, Nishi, SK, Muñoz-Martínez, J, Ordovás, JM, Daimiel, L. Use of different food classification systems to assess the association between ultra-processed food consumption and cardiometabolic health in an elderly population with metabolic syndrome (Predimed-plus cohort). Nutrients. 2021. 13. | Study Design; Intervention/Exposure
426 | Masley, Steven. Why the Mediterranean Diet Is the Best Diet on the Planet. Holistic Primary Care. 2020. 21:8–9. | Publication Status
427 | Massini, G, Capra, N, Buganza, R, Nyffenegger, A, de Sanctis, L, Guardamagna, O. Mediterranean Dietary Treatment in Hyperlipidemic Children: Should It Be an Option?. Nutrients. 2022. 14. | Intervention/Exposure; Health Status
428 | Mateo, KatrinaF. Evaluation of Intermittent Energy Restriction and Continuous Energy Restriction on Weight Loss and Blood Pressure Control in Overweight and Obese Patients With Hypertension. Journal of Clinical Outcomes Management. 2021. 28:256–259. doi:10.3389/fcvm.2021.750714 | Intervention/Exposure; Study Duration
429 | Matsumoto, S, Beeson, WL, Shavlik, DJ, Siapco, G, Jaceldo-Siegl, K, Fraser, G, Knutsen, SF. Association between vegetarian diets and cardiovascular risk factors in non-Hispanic white participants of the Adventist Health Study-2. Journal of Nutritional Science. 2019. doi:10.1017/jns.2019.1 | Intervention/Exposure
430 | Matthan, NR, Wylie-Rosett, J, Xue, X, Gao, Q, Groisman-Perelstein, AE, Diamantis, PM, Ginsberg, M, Mossavar-Rahmani, Y, Barger, K, Lichtenstein, AH. Effect of a family-based intervention on nutrient biomarkers, desaturase enzyme activities, and cardiometabolic risk factors in children with overweight and obesity. Current Developments in Nutrition. 2020. 4. doi:10.1093/CDN/NZZ138 | Intervention/Exposure
431 | Mazidi, M, Katsiki, N, Mikhailidis, DP, Banach, M. Effect of Dietary Insulinemia on All-Cause and Cause-Specific Mortality: Results From a Cohort Study. Journal of the American College of Nutrition. 2020. 39:407–413. doi:10.1080/07315724.2019.1646167 | Intervention/Exposure
432 | Mazidi, M, Katsiki, N, Mikhailidis, DP, Bartłomiejczyk, MA, Banach, M. Association of empirical dietary atherogenic indices with all-cause and cause-specific mortality in a multi-ethnic adult population of the United States. Nutrients. 2019. 11. doi:10.3390/nu11102323 | Intervention/Exposure
433 | Mazidi, M, Katsiki, N, Mikhailidis, DP, Sattar, N, Banach, M. Lower carbohydrate diets and all-cause and cause-specific mortality: A population-based cohort study and pooling of prospective studies. European Heart Journal. 2019. 40:2870–2879. doi:10.1093/eurheartj/ehz174 | Intervention/Exposure
434 | McArdle, CE, Bokhari, H, Rodell, CC, Buchanan, V, Preudhomme, LK, Isasi, CR, Graff, M, North, K, Gallo, LC, Pirzada, A, Daviglus, ML, Wojcik, G, Cai, J, Perreira, K, Fernandez-Rhodes, L. Findings from the Hispanic Community Health Study/Study of Latinos on the Importance of Sociocultural Environmental Interactors: Polygenic Risk Score-by-Immigration and Dietary Interactions. Frontiers in Genetics. 2021. 12. | Intervention/Exposure; Outcome
435 | McElfish, PA, Felix, HC, Bursac, Z, Rowland, B, Yeary, KHK, Long, CR, Selig, JP, Kaholokula, JK, Riklon, S. A Cluster Randomized Controlled Trial Comparing Diabetes Prevention Program Interventions for Overweight/Obese Marshallese Adults. Inquiry : a journal of medical care organization, provision and financing. 2023. 60:469580231152051. | Intervention/Exposure
436 | McEvoy CT, Moore SE, Erwin CM, Kontogianni M, Wallace SM, Appleton KM, Cupples ME, Hunter SJ, Kee F, McCance D, Patterson CC, Young IS, McKinley MC, Woodside JV. Trial to Encourage Adoption and Maintenance of a MEditerranean Diet (TEAM-MED): a randomised pilot trial of a peer support intervention for dietary behaviour change in adults from a Northern European population at high cardiovascular disease risk. | Intervention/Exposure; Comparator
437 | McKenzie, BL, Harris, K, Peters, SAE, Webster, J, Woodward, M. The association of energy and macronutrient intake with all-cause mortality, cardiovascular disease and dementia: findings from 120 963 women and men in the UK Biobank. Br J Nutr. 2021. 1–10. doi:10.1017/S000711452100266X | Intervention/Exposure
438 | Meadley, B, Wolkow, AP, Smith, K, Perraton, L, Bowles, KA, Bonham, MP. Cardiometabolic, dietary and physical health in graduate paramedics during the first 12-months of practice - a longitudinal study. Prehospital emergency care : official journal of the National Association of EMS Physicians and the National Association of State EMS Directors. 2021. 1–19. doi:10.1080/10903127.2021.1949081 | Intervention/Exposure; Outcome; Comparator
439 | Medenwald, D, Kluttig, A, Lacruz, ME, Schumann, J. Serum dietary fatty acids and coronary heart disease risk – A nested case-control-study within the CARLA cohort. Nutrition, Metabolism and Cardiovascular Diseases. 2019. 29:152–158. doi:10.1016/j.numecd.2018.10.006 | Study Design; Intervention/Exposure
440 | Mei S, Ding J, Wang K, Ni Z, Yu J. Mediterranean Diet Combined With a Low-Carbohydrate Dietary Pattern in the Treatment of Overweight Polycystic Ovary Syndrome Patients. 9. | Intervention/Exposure
441 | Meireles, CL, Du, Y, Li, S, Dennis, B, Niazi, NS, Patel, DI, Gelfond, JA, Li, C, Ye, H, Montellano, R, etal, . Individualized and Technology-Assisted Ketogenic Diet on Metabolic and Kidney Health in Overweight or Obese Adults. Journal of the American Society of Nephrology : JASN. 2022. 33:291-. doi:10.1681/asn.2021070948 | Publication Status
442 | Melero, V, Assaf-Balut, C, de la Torre, NG, Jiménez, I, Bordiú, E, Del Valle, L, Valerio, J, Familiar, C, Durán, A, Runkle, I, de Miguel, MP, Montañez, C, Barabash, A, Cuesta, M, Herraiz, MA, Izquierdo, N, Rubio, MA, Calle-Pascual, AL. Benefits of adhering to a mediterranean diet supplemented with extra virgin olive oil and pistachios in pregnancy on the health of offspring at 2 years of age. Results of the san carlos gestational diabetes mellitus prevention study. Journal of Clinical Medicine. 2020. 9. doi:10.3390/jcm9051454 | Data Overlap
443 | Menichini, D, Petrella, E, Dipace, V, Di Monte, A, Neri, I, Facchinetti, F. The impact of an early lifestyle intervention on pregnancy outcomes in a cohort of insulin-resistant overweight and obese women. Nutrients. 2020. 12. doi:10.3390/nu12051496 | Intervention/Exposure; Comparator
444 | Menotti A, Puddu PE, Catasta G. Determinants of longevity and age at death in a practically extinct cohort of middle-aged men followed-up for 61 years. | Outcome
445 | Merrotsy A, McCarthy AL, Lacey S, Coppinger T. Identifying dietary patterns in Irish schoolchildren and their association with nutritional knowledge and markers of health before and after intervention. 126. | Study Design; Intervention/Exposure
446 | Mi, B, Wen, X, Li, S, Liu, D, Lei, F, Liu, R, Shen, Y, Chen, Y, Zeng, L, Liu, X, Dang, S, Yan, H. Vegetable dietary pattern associated with low risk of preeclampsia possibly through reducing proteinuria. Pregnancy Hypertension. 2019. 16:131–138. doi:10.1016/j.preghy.2019.04.001 | Study Design
447 | Micek, A, Godos, J, Cernigliaro, A, Cincione, RI, Buscemi, S, Libra, M, Galvano, F, Grosso, G. Polyphenol-Rich and Alcoholic Beverages and Metabolic Status in Adults Living in Sicily, Southern Italy. Foods. 2021. 10. doi:10.3390/foods10020383 | Study Design; Intervention/Exposure
448 | Miller, Corrie, Benny, Paula, Boushey, Carol, Lee, Men-Jean. 818 Diet quality predicts hypertensive disorders of pregnancy in hawaii cohort. American Journal of Obstetrics & Gynecology. 2021. 224:S509-S509. doi:10.1016/j.ajog.2020.12.841 | Study Design; Publication Status
449 | Miller, ER, Alzahrani, HA, Bregaglio, DS, Christensen, JK, Palmer, SL, Alsharif, FH, Matroud, AS, Kanaani, KA, Sunbul, TJ, D’Almeida, J, Morrissey, S, Crockford, M, Rajanayagam, SN, Sarhan, AA, Azmi, WH, Miller, AR, Vrany, EA, Al Natour, S, Dalcin, AT, Ghamdi, MJ, Appel, LJ. Evaluation of a Video-Assisted Patient Education Program to Reduce Blood Pressure Delivered through the Electronic Medical Record: Results of a Quality Improvement Project. American Journal of Hypertension. 2021. 34:1328. | Intervention/Exposure; Study Duration
450 | Mills J, O’Dowd N. Healthy Diet and Physical Activity for Cardiovascular Disease Prevention in Adults with Cardiovascular Risk Factors. 104. | Study Design; Publication Status
451 | Minhas AS, Hong X, Wang G, Rhee DK, Liu T, Zhang M, Michos ED, Wang X, Mueller NT. Mediterranean-Style Diet and Risk of Preeclampsia by Race in the Boston Birth Cohort. | Study Design
452 | Mirmiran P, Hosseini-Esfahani F, Esfandiar Z, Hosseinpour-Niazi S, Azizi F. Associations between dietary antioxidant intakes and cardiovascular disease. 12. | Intervention/Exposure
453 | Mirmiran P, Houshialsadat Z, Bahadoran Z, Khalili-Moghadam S, Shahrzad MK, Azizi F. Dietary acid load and risk of cardiovascular disease: a prospective population-based study. 21. | Intervention/Exposure
454 | Mirmiran, P, Farhadnejad, H, Teymoori, F, Parastouei, K, Azizi, F. The higher adherence to healthy lifestyle factors is associated with a decreased risk of metabolic syndrome in Iranian adults. Nutrition bulletin. 2022. 47:57. | Intervention/Exposure; Outcome
455 | Mirmiran, P, Ziadlou, M, Karimi, S, Hosseini-Esfahani, F, Azizi, F. The association of dietary patterns and adherence to WHO healthy diet with metabolic syndrome in children and adolescents: Tehran lipid and glucose study. BMC Public Health. 2019. 19:1457. doi:10.1186/s12889-019-7779-9 | Intervention/Exposure; Outcome; Comparator
456 | Miyagawa N. Dietary Intake of Manganese in the Japanese Diet and its Association with Cardiometabolic and Cardiovascular Diseases. | Study Design; Publication Status
457 | Mohammadi, F, Mirzaei, K, Rahimi, MH, Mollahosesini, M, Issah, A, Yekaninejad, MS, Maghbooli, Z. Alternative Healthy Eating Index may be associated with liver enzymes level among healthy adults. Progress in Nutrition. 2019. 21:165–169. doi:10.23751/pn.v21i2-S.7190 | Study Design
458 | Mohorko, N, Černelič-Bizjak, M, Poklar-Vatovec, T, Grom, G, Kenig, S, Petelin, A, Jenko-Pražnikar, Z. Weight loss, improved physical performance, cognitive function, eating behavior, and metabolic profile in a 12-week ketogenic diet in obese adults. Nutrition Research. 2019. 62:64–77. doi:10.1016/j.nutres.2018.11.007 | Study Design; Intervention/Exposure
459 | Mohsenzadeh-Ledari, Farideh, Taghizadeh, Ziba, Motaghi, Zahra, Keramat, Afsaneh, Moosazadeh, Mahmood, Yazdani, Shahla, Najafi, Ali, Ghorbani, Mayam. Effect of caring intervention on preeclampsia in pregnant women with metabolic syndrome: A randomized controlled trial. Journal of Nursing & Midwifery Sciences. 2022. 9:8–15. doi:10.4103/jnms.jnms_49_21 | Intervention/Exposure; Comparator
460 | Mokhtari, Z, Sharafkhah, M, Poustchi, H, Sepanlou, SG, Khoshnia, M, Gharavi, A, Sohrabpour, AA, Sotoudeh, M, Dawsey, SM, Boffetta, P, Abnet, CC, Kamangar, F, Etemadi, A, Pourshams, A, FazeltabarMalekshah, A, Islami, F, Brennan, P, Malekzadeh, R, Hekmatdoost, A. Adherence to the Dietary Approaches to Stop Hypertension (DASH) diet and risk of total and cause-specific mortality: results from the Golestan Cohort Study. Int J Epidemiol. 2019. 48:1824–1838. doi:10.1093/ije/dyz079 | Country
461 | Molina-Leyva, A, Cuenca-Barrales, C, Vega-Castillo, JJ, Ruiz-Carrascosa, JC, Ruiz-Villaverde, R. Adherence to Mediterranean diet in Spanish patients with psoriasis: Cardiovascular benefits?. Dermatologic Therapy. 2019. 32. doi:10.1111/dth.12810 | Study Design
462 | Moller, SP, Mejborn, H, Christensen, AI, Biltoft-Jensen, A, Thygesen, LC. Meat consumption, stratified by dietary quality, and risk of heart disease. Br J Nutr. 2021. 1–7. doi:10.1017/S0007114521000623 | Intervention/Exposure
463 | Momiyama Y, Kishimoto Y, Saita E, Aoyama M, Ohmori R, Kondo K. Association between the Japanese Diet and Coronary Artery Disease in Patients Undergoing Coronary Angiography. 15. | Study Design
464 | Monge, A, Silva Canella, D, Lopez-Olmedo, N, Lajous, M, Cortes-Valencia, A, Stern, D. Ultraprocessed beverages and processed meats increase the incidence of hypertension in Mexican women. Br J Nutr. 2021. 126:600–611. doi:10.1017/S0007114520004432 | Intervention/Exposure
465 | Monserrat-Mesquida M, Quetglas-Llabrés M, Bouzas C, García S, Mateos D, Gómez C, Gámez JM, Poulsen HE, Tur JA, Sureda A. Effects of 2-Year Nutritional and Lifestyle Intervention on Oxidative and Inflammatory Statuses in Individuals of 55 Years of Age and over at High Cardiovascular Risk. 11. | Intervention/Exposure; Comparator
466 | Morales E, García-Serna AM, Larqué E, Sánchez-Campillo M, Serrano-Munera A, Martinez-Graciá C, Santaella-Pascual M, Suárez-Martínez C, Vioque J, Noguera-Velasco JA, Avilés-Plaza FV, Martínez-Villanueva M, Ballesteros-Meseguer C, Galdo-Castiñeira L, García-Marcos L. Dietary Patterns in Pregnancy and Biomarkers of Oxidative Stress in Mothers and Offspring: The NELA Birth Cohort. 9. | Outcome
467 | Morales Suárez-Varela M, Peraita-Costa I, Marín AP, Marcos Puig B, Llopis-Morales A, Soriano JM. Mediterranean Dietary Pattern and Cardiovascular Risk in Pregnant Women. 13. | Study Design; Outcome
468 | Mora-Urda AI, Martín-Almena FJ, Montero López MDP. Relationship between the Dietary Inflammatory Index and Cardiovascular Health among Children. 19. | Study Design
469 | Mouodi, S, Hosseini, SR, Ghadimi, R, Cumming, RG, Bijani, A, Mouodi, M, Pasha, YZ. Lifestyle interventions to promote healthy nutrition and physical activity in middle-age (40–60 years) adults: A randomized controlled trial in the North of Iran. Journal of Research in Health Sciences. 2019. 19. doi:10.15171/jrhs.2019.01 | Intervention/Exposure
470 | Mu, L, Yu, P, Xu, H, Gong, T, Chen, D, Tang, J, Zou, Y, Rao, H, Mei, Y, Mu, L. Efecto de la reducción de sodio basada en la dieta DASH sobre la presión arterial en pacientes hipertensos con diabetes de tipo 2. Effect of sodium reduction based on the DASH diet on blood pressure in hypertensive patients with type 2 diabetes. 2022. | Health Status
471 | Mulcahy, MC, Tellez-Rojo, MM, Cantoral, A, Solano-González, M, Baylin, A, Bridges, D, Peterson, KE, Perng, W. Maternal Carbohydrate Intake During Pregnancy is Associated with Child Peripubertal Markers of Metabolic Health but not Adiposity. Public health nutrition. 2021. 1. | Intervention/Exposure; Outcome
472 | Muntner, P, Jaeger, BC, Hardy, ST, Foti, K, Reynolds, K, Whelton, PK, Bowling, CB. Age-specific prevalence and factors associated with normal blood pressure among US adults. American journal of hypertension. 2021. | Study Design; Intervention/Exposure
473 | Muralidharan J, Moreno-Indias I, Bulló M, Lopez JV, Corella D, Castañer O, Vidal J, Atzeni A, Fernandez-García JC, Torres-Collado L, Fernández-Carrión R, Fito M, Olbeyra R, Gomez-Perez AM, Galiè S, Bernal-López MR, Martinez-Gonzalez MA, Salas-Salvadó J, Tinahones FJ. Effect on gut microbiota of a 1-y lifestyle intervention with Mediterranean diet compared with energy-reduced Mediterranean diet and physical activity promotion: PREDIMED-Plus Study. 114. | Intervention/Exposure; Outcome
474 | Murff HJ. In patients with CHD, a Mediterranean vs. low-fat diet reduced major CV events at 7 y. | Health Status
475 | Muscogiuri, G, Barrea, L, Di Somma, C, Altieri, B, Vecchiarini, M, Orio, F, Spinosa, T, Colao, A, Savastano, S. Patient empowerment and the Mediterranean diet as a possible tool to tackle prediabetes associated with overweight or obesity: a pilot study. Hormones. 2019. 18:75–84. doi:10.1007/s42000-018-0090-9 | Study Design
476 | Myhrstad, MC, de Mello, VD, Dahlman, I, Kolehmainen, M, Paananen, J, Rundblad, A, Carlberg, C, Olstad, OK, Pihlajamäki, J, Holven, KB, Hermansen, K, Dragsted, LO, Gunnarsdottir, I, Cloetens, L, Storm, MU, . Healthy Nordic Diet Modulates the Expression of Genes Related to Mitochondrial Function and Immune Response in Peripheral Blood Mononuclear Cells from Subjects with the Metabolic Syndrome-A SYSDIET Sub-Study. Molecular nutrition & food research. 2019. e1801405. doi:10.1002/mnfr.201801405 | Intervention/Exposure; Comparator
477 | Na M, Wang Y, Zhang X, Sarpong C, Kris-Etherton PM, Gao M, Xing A, Wu S, Gao X. DASH-style Dietary Pattern and 24-hour Ambulatory Blood Pressure in Elderly Chinese with or without Hypertension. | Study Design
478 | Na M, Wang Y, Zhang X, Sarpong C, Kris-Etherton PM, Gao M, Xing A, Wu S, Gao X. Dietary Approaches to Stop Hypertension (DASH)-Style Dietary Pattern and 24-Hour Ambulatory Blood Pressure in Elderly Chinese with or without Hypertension. 152. | Study Design
479 | Naghizadeh, A, Zargaran, A, Karimi, M. The Heart-Healthy Avicennian Diet for Prevention of Heart Disease. Eur Heart J. 2020. 41:1465–1466. doi:10.1093/eurheartj/ehaa125 | Study Design; Publication Status
480 | Naghshi, S, Sadeghi, O. Current evidence on dietary intakes of fatty acids and mortality. The BMJ. 2021. 375. | Study Design
481 | Nah, EH, Chu, J, Kim, S, Cho, S, Kwon, E. Efficacy of lifestyle interventions in the reversion to normoglycemia in Korean prediabetics: One-year results from a randomised controlled trial. Primary Care Diabetes. 2019. 13:212–220. doi:10.1016/j.pcd.2018.11.017 | Intervention/Exposure
482 | Nct, . Low Carbohydrate Diet Versus Low Fat Diet in Reversing the Metabolic Syndrome Using NCEP ATP III Criteria. https://clinicaltrials.gov/show/NCT04681924. 2020. | Publication Status
483 | Nct, . Randomized Controlled Multi-center Study of the New Nordic Diet in Gestational Diabetes Mellitus. https://clinicaltrials.gov/show/NCT04169243. 2019. | Study Design; Publication Status
484 | Nct, . The Effect of the DASH Diet Containing Meat on Muscle and Metabolic Health in Older Adults. https://clinicaltrials.gov/show/NCT04127240. 2019. | Publication Status
485 | Nct, . The Impact of Consumption of Eggs in the Context of Plant-Based Diets on Endothelial Function, Diet Quality, and Cardio-Metabolic Risk Factors in Adults at Risk for Type 2 Diabetes. https://clinicaltrials.gov/show/NCT04316429. 2020. | Study Duration; Publication Status
486 | NCT04252105, . Antioxidant-rich Diet and Oxidative Stress in Healthy Preschoolers. 2020. | Publication Status
487 | Ngai, C, Ganguzza, L, Flink, L, Woolf, K, Guo, Y, Acosta, V, Gianos, E, Slater, J, Burdowski, J, Shah, B. Comparison of Dietary Patterns, Perceptions of Health, and Perceived Barriers to a Heart Healthy Diet Before and After Coronary Artery Angiography. American Journal of Cardiology. 2019. 123:865–873. doi:10.1016/j.amjcard.2018.11.056 | Intervention/Exposure; Health Status
488 | Ngo Njembe, MoniqueT, Pachikian, Barbara, Lobysheva, Irina, Van Overstraeten, Nancy, Dejonghe, Louis, Verstraelen, Eleonore, Buchet, Marine, Rasse, Catherine, Gardin, Cécile, Mignolet, Eric, Balligand, Jean-Luc, Larondelle, Yvan, Chiva-Blanch, Gemma, Cofán, Montserrat. A Three-Month Consumption of Eggs Enriched with ω-3, ω-5 and ω-7 Polyunsaturated Fatty Acids Significantly Decreases the Waist Circumference of Subjects at Risk of Developing Metabolic Syndrome: A Double-Blind Randomized Controlled Trial. Nutrients. 2021. 13:663–663. doi:10.3390/nu13020663 | Intervention/Exposure
489 | Nielsen, Tine Bjerg, Würtz, Anne Mette Lund, Tjønneland, Anne, Overvad, Kim, Dahm, Christina Catherine. Substitution of unprocessed and processed red meat with poultry or fish and total and cause-specific mortality. British Journal of Nutrition. 2022. 127:563–569. doi:10.1017/S0007114521001252 | Intervention/Exposure
490 | Nirdnoy N, Sranacharoenpong K, Surawit A, Pinsawas B, Mongkolsucharitkul P, Pongkunakorn T, Manosan T, Ophakas S, Suta S, Pumeiam S, Mayurasakorn K. Validation of a Thai semiquantitative food frequency questionnaire (semi-FFQ) for people at risk of metabolic syndrome. 42. | Study Design
491 | Nishi SK, Babio N, Gómez-Martínez C, Martínez-González MÁ, Ros E, Corella D, Castañer O, Martínez JA, Alonso-Gómez ÁM, Wärnberg J, Vioque J, Romaguera D, López-Miranda J, Estruch R, Tinahones FJ, Lapetra J, Serra-Majem JL, Bueno-Cavanillas A, Tur JA, Martín Sánchez V, Pintó X, Delgado-Rodríguez M, Matía-Martín P, Vidal J, Vázquez C, Daimiel L, Razquin C, Coltell O, Becerra-Tomás N, De La Torre Fornell R, Abete I, Sorto-Sanchez C, Barón-López FJ, Signes-Pastor AJ, Konieczna J, Garcia-Rios A, Casas R, Gomez-Perez AM, Santos-Lozano JM, García-Arellano A, Guillem-Saiz P, Ni J, Trinidad Soria-Florido M, Zulet MÁ, Vaquero-Luna J, Toledo E, Fitó M, Salas-Salvadó J. Mediterranean, DASH, and MIND Dietary Patterns and Cognitive Function: The 2-Year Longitudinal Changes in an Older Spanish Cohort. 13. | Outcome
492 | Noakes, TD. Hiding unhealthy heart outcomes in a low-fat diet trial: the Women’s Health Initiative Randomized Controlled Dietary Modification Trial finds that postmenopausal women with established coronary heart disease were at increased risk of an adverse outcome if they consumed a low-fat ‘heart-healthy’ diet. Open Heart. 2021. 8. doi:10.1136/openhrt-2021-001680 | Study Design
493 | Noerman, S, Kokla, M, Koistinen, VM, Lehtonen, M, Tuomainen, TP, Brunius, C, Virtanen, JK, Hanhineva, K. Associations of the serum metabolite profile with a healthy Nordic diet and risk of coronary artery disease. Clin Nutr. 2021. 40:3250–3262. doi:10.1016/j.clnu.2020.10.051 | Intervention/Exposure; Comparator
494 | Normayanti, , Suparyatmo, JB, Prayitno, A. The Effect of Nutrition Education on Body Mass Index, Waist Circumference, Mid-upper Arm Circumference and Blood Pressure in Obese Adolescents. Electronic Journal of General Medicine. 2020. 17:1–8. doi:10.29333/ejgm/7884 | Intervention/Exposure
495 | Nouri, F, Sadeghi, M, Mohammadifard, N, Roohafza, H, Feizi, A, Sarrafzadegan, N. Longitudinal association between an overall diet quality index and latent profiles of cardiovascular risk factors: results from a population based 13-year follow up cohort study. Nutr Metab (Lond). 2021. 18:28. doi:10.1186/s12986-021-00560-5 | Outcome
496 | Nurwanti, E, Bai, CH. Impact of web-based health promotion program and online nutrition education intervention for metabolic syndrome patients: effects on lipid profiles and inflammation. Annals of nutrition & metabolism. 2019. 75:325–326. doi:10.1159/000501751 | Publication Status
497 | Obomsawin, A, D’Amico, D, Fiocco, AJ. The association between Mediterranean diet adherence and allostatic load in older adults. Psychoneuroendocrinology. 2022. 143. | Study Design
498 | O’Driscoll, T, Minty, R, Poirier, D, Poirier, J, Hopman, W, Willms, H, Goertzen, A, Madden, S, Kelly, L. New obesity treatment: Fasting, exercise and low carb diet - The NOT-FED study. Canadian journal of rural medicine : the official journal of the Society of Rural Physicians of Canada = Journal canadien de la medecine rurale : le journal officiel de la Societe de medecine rurale du Canada. 2021. 26:55–60. doi:10.4103/CJRM.CJRM_1_20 | Study Design
499 | Oh SW, Wood AC, Hwang SS, Allison M. Racial and Ethnic Differences in the Association of Low-Carbohydrate Diet With Mortality in the Multi-Ethnic Study of Atherosclerosis. 5. | Intervention/Exposure
500 | O’Hearn M, Erndt-Marino J, Gerber S, Lauren BN, Economos C, Wong JB, Blumberg JB, Mozaffarian D. Validation of Food Compass with a healthy diet, cardiometabolic health, and mortality among U.S. adults, 1999–2018. 13. | Outcome
501 | Ohman, EA, Kirchner, L, Winkvist, A, Bertz, F, Holven, KB, Ulven, SM, Brekke, HK. Effects of dietary and exercise treatments on HDL subclasses in lactating women with overweight and obesity: a secondary analysis of a randomised controlled trial. British Journal of Nutrition. 2022. 128:2105. | Intervention/Exposure
502 | Ojeda-Granados C, Panduro A, Gonzalez-Aldaco K, Rivera-Iñiguez I, Campos-Medina L, Roman S. Adherence to a Fish-Rich Dietary Pattern Is Associated with Chronic Hepatitis C Patients Showing Low Viral Load: Implications for Nutritional Management. 13. | Health Status; Outcome
503 | Okuda M, Fujiwara A, Sasaki S. Adherence to the Japanese Food Guide: The Association between Three Scoring Systems and Cardiometabolic Risks in Japanese Adolescents. 14. | Study Design
504 | Oliveira, Camila, Silveira, Erika Aparecida, Rosa, Lorena, Santos, Annelisa, Rodrigues, Ana Paula, Mendonça, Carolina, Silva, Lucas, Gentil, Paulo, Rebelo, Ana Cristina. Risk Factors Associated with Cardiac Autonomic Modulation in Obese Individuals. Journal of Obesity. 2020. 1–8. doi:10.1155/2020/7185249 | Study Design
505 | O’Neill RF, McGowan L, McEvoy CT, Wallace SM, Moore SE, McKinley MC, Kee F, Cupples ME, Young IS, Woodside JV. The feasibility of a peer support intervention to encourage adoption and maintenance of a Mediterranean diet in established community groups at increased CVD risk: the TEAM-MED EXTEND study: a pilot cluster randomised controlled trial. | Intervention/Exposure; Outcome; Comparator
506 | Ooi, DSQ, Toh, JY, Ng, LYB, Peng, Z, Yang, S, Rashid, NSBSA, Sng, AA, Chan, YH, Chong, MF-F, Lee, YS. Dietary Intakes and Eating Behavior between Metabolically Healthy and Unhealthy Obesity Phenotypes in Asian Children and Adolescents. Nutrients. 2022. 14. | Study Design
507 | Ooi, EMM, Lichtenstein, AH, Millar, JS, Diffenderfer, MR, Lamon-Fava, S, Rasmussen, H, Welty, FK, Barrett, PHR, Schaefer, EJ. Effects of therapeutic lifestyle change diets high and low in dietary fish-derived FAs on lipoprotein metabolism in middle-aged and elderly subjects. Journal of Lipid Research. 2012. 53:1958. | Intervention/Exposure
508 | Oppezzo M, Knox M, Skan J, Chieng A, Crouch M, Aikens RC, Benowitz NL, Schnellbaecher M, Prochaska JJ. Traditional Heart-Healthy Diet and Medication Adherence in the Norton Sound Region: An 18-Month Telehealth Intervention. 19. | Intervention/Exposure; Comparator
509 | Osorio-Conles, Ó, Olbeyra, R, Moizé, V, Ibarzabal, A, Giró, O, Viaplana, J, Jiménez, A, Vidal, J, de Hollanda, A. Positive Effects of a Mediterranean Diet Supplemented with Almonds on Female Adipose Tissue Biology in Severe Obesity. Nutrients. 2022. 14. | Intervention/Exposure; Outcome
510 | Otsuka, R, Tange, C, Nishita, Y, Kato, Y, Tomida, M, Imai, T, Ando, F, Shimokata, H. Dietary Diversity and All-Cause and Cause-Specific Mortality in Japanese Community-Dwelling Older Adults. Nutrients. 2020. 12. doi:10.3390/nu12041052 | Intervention/Exposure
511 | Ozner, Michael. THE MEDITERRANEAN DIET: A Prescription for Healthy Aging and Longevity. Life Extension. 2021. 27:66–74. | Study Design; Publication Status
512 | Pagliai, G, Russo, E, Niccolai, E, Dinu, M, Di Pilato, V, Magrini, A, Bartolucci, G, Baldi, S, Menicatti, M, Giusti, B, etal, . Influence of a 3-months low-calorie Mediterranean diet vs. Vegetarian diet on human gut microbiota and SCFA: the CARDIVEG Study. Proceedings of the Nutrition Society. 2020. 79. doi:10.1017/S0029665120001251 | Publication Status
513 | Pagliai, G, Russo, E, Niccolai, E, Dinu, M, Di Pilato, V, Magrini, A, Bartolucci, G, Baldi, S, Menicatti, M, Giusti, B, Marcucci, R, Rossolini, GM, Casini, A, Sofi, F, Amedei, A. Influence of a 3-month low-calorie Mediterranean diet compared to the vegetarian diet on human gut microbiota and SCFA: the CARDIVEG Study. Eur J Nutr. 2020. 59:2011–2024. doi:10.1007/s00394-019-02050-0 | Intervention/Exposure; Outcome
514 | Pahkala, K, Laitinen, TT, Niinikoski, H, Kartiosuo, N, Rovio, SP, Lagstrom, H, Loo, BM, Salo, P, Jokinen, E, Magnussen, CG, Juonala, M, Simell, O, Jula, A, Ronnemaa, T, Viikari, J, Raitakari, OT. Effects of 20-year infancy-onset dietary counselling on cardiometabolic risk factors in the Special Turku Coronary Risk Factor Intervention Project (STRIP): 6-year post-intervention follow-up. Lancet Child Adolesc Health. 2020. 4:359–369. doi:10.1016/S2352-4642(20)30059-6 | Intervention/Exposure
515 | Paik, JK, Park, M, Shin, JE, Jang, SY, Shin, JY. Dietary Protein to Carbohydrate Ratio and Incidence of Metabolic Syndrome in Korean Adults Based on a Long-Term Prospective Community-Based Cohort. Nutrients. 2020. 12. doi:10.3390/nu12113274 | Intervention/Exposure
516 | Pan F, Wang Z, Wang H, Zhang J, Su C, Jia X, Du W, Jiang H, Li W, Wang L, Hao L, Zhang B, Ding G. Association between Ultra-Processed Food Consumption and Metabolic Syndrome among Adults in China-Results from the China Health and Nutrition Survey. 15. | Intervention/Exposure; Country
517 | Panagiotakos, Demosthenes, Kouvari, Matina, Chrysohoou, Christina, Georgousopoulou, Ekavi, Tousoulis, Dimitrios, Pitsavos, Christos. THE ASSOCIATION BETWEEN HEALTHFUL AND UNHEALTHFUL PLANT BASED DIETARY PATTERNS AND 10-YEAR CARDIOVASCULAR DISEASE INCIDENCE IN APPARENTLY HEALTHY MEN AND WOMEN: HIGHLIGHTS FROM THE ATTICA PROSPECTIVE (2002–2012) STUDY. Journal of the American College of Cardiology (JACC). 2020. 75:9–9. doi:10.1016/S0735-1097(20)30555-6 | Publication Status
518 | Paoli, A, Mancin, L, Giacona, MC, Bianco, A, Caprio, M. Effects of a ketogenic diet in overweight women with polycystic ovary syndrome. J Transl Med. 2020. 18:104. doi:10.1186/s12967-020-02277-0 | Study Design; Health Status
519 | Papandreou, C, Becerra-Tomás, N, Bulló, M, Martínez-González, Á M, Corella, D, Estruch, R, Ros, E, Arós, F, Schroder, H, Fitó, M, Serra-Majem, L, Lapetra, J, Fiol, M, Ruiz-Canela, M, Sorli, JV, Salas-Salvadó, J. Legume consumption and risk of all-cause, cardiovascular, and cancer mortality in the PREDIMED study. Clinical Nutrition. 2019. 38:348–356. doi:10.1016/j.clnu.2017.12.019 | Intervention/Exposure
520 | Park SY, Kang M, Shvetsov YB, Setiawan VW, Boushey CJ, Haiman CA, Wilkens LR, Le Marchand L. Diet quality and all-cause and cancer-specific mortality in cancer survivors and non-cancer individuals: the Multiethnic Cohort Study. | Health Status; Outcome
521 | Park, S, Kang, S. A Western-style diet interacts with genetic variants of the LDL receptor to hyper-LDL cholesterolemia in Korean adults. Public Health Nutr. 2021. 24:2964–2974. doi:10.1017/S1368980020001305 | Comparator
522 | Park, S, Zhang, T. A positive association of overactivated immunity with metabolic syndrome risk and mitigation of its association by a plant-based diet and physical activity in a large cohort study. Nutrients. 2021. 13. doi:10.3390/nu13072308 | Intervention/Exposure; Outcome; Comparator
523 | Park, YMM, Choi, MK, Lee, SS, Shivappa, N, Han, K, Steck, SE, Hébert, JR, Merchant, AT, Sandler, DP. Dietary inflammatory potential and risk of mortality in metabolically healthy and unhealthy phenotypes among overweight and obese adults. Clinical Nutrition. 2019. 38:682–688. doi:10.1016/j.clnu.2018.04.002 | Intervention/Exposure
524 | Parlapani, E, Agakidis, C, Karagiozoglou-Lampoudi, T, Sarafidis, K, Agakidou, E, Athanasiadis, A, Diamanti, E. The Mediterranean diet adherence by pregnant women delivering prematurely: association with size at birth and complications of prematurity. Journal of Maternal-Fetal and Neonatal Medicine. 2019. 32:1084–1091. doi:10.1080/14767058.2017.1399120 | Study Design; Health Status
525 | Pasta, A, Formisano, E, Cremonini, AL, Maganza, E, Parodi, E, Piras, S, Pisciotta, L. Diet and Nutraceutical Supplementation in Dyslipidemic Patients: First Results of an Italian Single Center Real-World Retrospective Analysis. Nutrients. 2020. 12. doi:10.3390/nu12072056 | Study Design; Intervention/Exposure; Comparator
526 | Pauley, M, Mays, C, Bailes, JR, Schwartzman, ML, Castle, M, McCoy, M, Patick, C, Preston, D, Nudelman, MJR, Denning, KL, Bellner, L, Werthammer, J. Carbohydrate-Restricted Diet: A Successful Strategy for Short-Term Management in Youth with Severe Obesity-An Observational Study. Metabolic Syndrome and Related Disorders. 2021. 19:281–287. doi:10.1089/met.2020.0078 | Study Design; Intervention/Exposure
527 | Pérez-Rodrigo C, Hervás Bárbara G, Gianzo Citores M, Aranceta-Bartrina J. Prevalence of obesity and associated cardiovascular risk factors in the Spanish population: the ENPE study. 75. | Study Design
528 | Perry CA, Van Guilder GP, Butterick TA. Decreased myostatin in response to a controlled DASH diet is associated with improved body composition and cardiometabolic biomarkers in older adults: results from a controlled-feeding diet intervention study. 8. | Outcome
529 | Perry, CA, Van Guilder, GP, Hossain, M, Kauffman, A. Cardiometabolic Changes in Response to a Calorie-Restricted DASH Diet in Obese Older Adults. Front Nutr. 2021. 8:647847. doi:10.3389/fnut.2021.647847 | Comparator
530 | Perry, CA, Van Guilder, GP, Kauffman, A, Hossain, M. A Calorie-Restricted DASH Diet Reduces Body Fat and Maintains Muscle Strength in Obese Older Adults. Nutrients. 2019. 12. doi:10.3390/nu12010102 | Study Design
531 | Pestoni, G, Karavasiloglou, N, Braun, J, Krieger, JP, Sych, JM, Bopp, M, Faeh, D, Gruebner, O, Rohrmann, S. Does diet map with mortality? Ecological association of dietary patterns with chronic disease mortality and its spatial dependence in Switzerland. Br J Nutr. 2021. 1–13. doi:10.1017/S0007114521001525 | Study Design
532 | Petermann-Rocha, Fanny, Gray, StuartR, Pell, Jill, Celis-Morales, Carlos. Diet-quality and its association with cardiovascular diseases and cancer incidence and all-cause mortality: a prospective cohort study from UK Biobank. Proceedings of the Nutrition Society. 2020. 79:1–1. doi:10.1017/S0029665120000208 | Publication Status
533 | Petersen JM, Naimi AI, Kirkpatrick SI, Bodnar LM. Equal Weighting of the Healthy Eating Index-2010 Components May not be Appropriate for Pregnancy. | Outcome
534 | Petersen KS, Murphy J, Whitbread J, Clifton PM, Keogh JB. The Effect of a Peanut-Enriched Weight Loss Diet Compared to a Low-Fat Weight Loss Diet on Body Weight, Blood Pressure, and Glycemic Control: A Randomized Controlled Trial. 14. | Intervention/Exposure
535 | Phillips, NE, Mareschal, J, Schwab, N, Manoogian, ENC, Borloz, S, Ostinelli, G, Gauthier-Jaques, A, Umwali, S, Gonzalez Rodriguez, E, Aeberli, D, Hans, D, Panda, S, Rodondi, N, Naef, F, Collet, TH. The Effects of Time-Restricted Eating versus Standard Dietary Advice on Weight, Metabolic Health and the Consumption of Processed Food: A Pragmatic Randomised Controlled Trial in Community-Based Adults. Nutrients. 2021. 13. doi:10.3390/nu13031042 | Intervention/Exposure; Study Duration
536 | Piccirillo F, Miano N, Goffredo C, Nusca A, Mangiacapra F, Khazrai YM, De Gara L, Ussia GP, Grigioni F. Impact of Mediterranean diet on metabolic and inflammatory status of patients with polyvascular atherosclerotic disease. | Health Status
537 | Pintó, X, Fanlo-Maresma, M, Corbella, E, et al. A Mediterranean Diet Rich in Extra-Virgin Olive Oil Is Associated with a Reduced Prevalence of Nonalcoholic Fatty Liver Disease in Older Individuals at High Cardiovascular Risk. Journal of Nutrition. 2019. 149:1920. | Outcome
538 | Piovesan CH, Gustavo A, Macagnan FE, Saboya PP, Oliveira MDS, Bodanese LC, Ludwig MWB, Closs VE, Feoli AMP. The Effect of Different Interventions for Lifestyle Modifications on the Number of Diagnostic Criteria and Clinical Aspects of Metabolic Syndrome. 19. | Intervention/Exposure
539 | Pisanu, S, Palmas, V, Madau, V, Casula, E, Deledda, A, Cusano, R, Uva, P, Vascellari, S, Boi, F, Loviselli, A, Manzin, A, Velluzzi, F. Impact of a moderately hypocaloric mediterranean diet on the gut microbiota composition of italian obese patients. Nutrients. 2020. 12:1–19. doi:10.3390/nu12092707 | Study Design; Comparator
540 | Porter Starr, KN, Connelly, MA, Orenduff, MC, McDonald, SR, Sloane, R, Huffman, KM, Kraus, WE, Bales, CW. Impact on cardiometabolic risk of a weight loss intervention with higher protein from lean red meat: Combined results of 2 randomized controlled trials in obese middle-aged and older adults. Journal of Clinical Lipidology. 2019. 13:920–931. doi:10.1016/j.jacl.2019.09.012 | Intervention/Exposure
541 | Prentice, RL, Aragaki, AK, Van Horn, L, Thomson, CA, Tinker, LF, Manson, JE, Mossavar-Rahmani, Y, Huang, Y, Zheng, C, Beresford, SAA, Wallace, R, Anderson, GL, Lampe, JW, Neuhouser, ML. Mortality Associated with Healthy Eating Index Components and an Empirical-scores Healthy Eating Index in a Cohort of Postmenopausal Women. The Journal of nutrition. 2022. | Intervention/Exposure; Outcome
542 | Primo, D, Izaola, O, de Luis, D. Effects of a high protein/low carbohydrate low-calorie diet versus a standard low-calorie diet on anthropometric parameters and cardiovascular risk factors, role of polymorphism rs3123554 in the cannabinoid receptor gene type 2 (CB2R). Endocrinologia, Diabetes y Nutricion. 2020. 67:446–453. doi:10.1016/j.endinu.2019.09.010 | Intervention/Exposure
543 | Priya Margaret, A, Ramesh, S, Sundari, S. Prevalence of hypertension and its correlation with diet in school going adolescent girls in an urban setting. Indian Journal of Public Health Research and Development. 2019. 10:1504–1506. doi:10.5958/0976-5506.2019.03748.3 | Study Design; Country
544 | Psota, TL, Tindall, AM, Lohse, B, Miller, PE, Petersen, KS, Kris-Etherton, PM. The Weight Optimization Revamping Lifestyle using the Dietary Guidelines (WORLD) Study: Sustained Weight Loss Over 12 Months. Obesity. 2020. 28:1235–1244. doi:10.1002/oby.22824 | Intervention/Exposure
545 | Purnamasari, SD, Hsu, C-Y, Chen, Y-T, Kurniawan, AL, Lee, H-A, Chao, JC-J. Combined Low Plant and High Animal Dietary Pattern Is Associated with a Lower Risk of Anemia among Dyslipidemic Adult Women in Taiwan: A Retrospective Study from 2001 to 2015. International Journal of Environmental Research and Public Health. 2022. 19. | Study Design
546 | Qin, C, Lv, J, Yu, C, Guo, Y, Bian, Z, Gao, M, Du, H, Yang, L, Chen, Y, Shen, L, Zhou, S, Chen, J, Chen, Z, Li, L. Dietary patterns and cardiometabolic diseases in 0.5 million Chinese adults: a 10-year cohort study. Nutrition Journal. 2021. 20. | Country
547 | Quetglas-Llabrés MM, Monserrat-Mesquida M, Bouzas C, Gómez C, Mateos D, Ripoll-Vera T, Tur JA, Sureda A. Inflammatory and Oxidative Stress Markers Related to Adherence to the Mediterranean Diet in Patients with Metabolic Syndrome. 11. | Study Design
548 | Rabbani B, Chiti H, Sharifi F, Mazloomzadeh S. Effect of lifestyle modification for two years on obesity and metabolic syndrome components in elementary students: A community-based trial. 13. | Intervention/Exposure; Comparator
549 | Rahman VJ, Horberg MA, Hu H, Vupputuri S. Implementation of a Plant-Based, Nutrition Program in a Large Integrated Health Care System: Results of a Pilot Program. 12. | Study Design
550 | Rashidmayvan, M, Sharifan, P, Darroudi, S, Saffar Soflaei, S, Salaribaghoonabad, R, Safari, N, Yousefi, M, Honari, M, Ghazizadeh, H, Ferns, G, Esmaily, H, Ghayour-Mobarhan, M. Association between dietary patterns and body composition in normal-weight subjects with metabolic syndrome. Journal of Diabetes and Metabolic Disorders. 2022. | Study Design
551 | Rassy N, Van Straaten A, Carette C, Hamer M, Rives-Lange C, Czernichow S. Association of Healthy Lifestyle Factors and Obesity-Related Diseases in Adults in the UK. 6. | Intervention/Exposure; Outcome
552 | Raza, Q, Nicolaou, M, Cay, F, Seidell, J. Association of dietary intake and dietary habits with risk of cardiovascular disease among immigrant Pakistanis living in the Netherlands. Journal of the Pakistan Medical Association. 2021. 71:219–227. doi:10.47391/JPMA.219 | Study Design
553 | Razquin C, Ruiz-Canela M, Wernitz A, Toledo E, Corella D, Alonso-Gómez Á, Fitó M, Gómez-Gracia E, Estruch R, Fiol M, Lapetra J, Serra-Majem L, Ros E, Arós F, Salas-Salvadó J, Schulze MB, Martinez-Gonzalez MA. Effects of Supplemented Mediterranean Diets on Plasma-Phospholipid Fatty Acid Profiles and Risk of Cardiovascular Disease after 1 Year of Intervention in the PREDIMED Trial. | Intervention/Exposure
554 | Razquin, C, Ruiz-Canela, M, Toledo, E, Hernandez-Alonso, P, Clish, CB, Guasch-Ferre, M, Li, J, Wittenbecher, C, Dennis, C, Alonso-Gomez, A, etal, . Metabolomics of the tryptophan-kynurenine degradation pathway and risk of atrial fibrillation and heart failure: potential modification effect of Mediterranean diet. American journal of clinical nutrition. 2021. doi:10.1093/ajcn/nqab238 | Study Design; Intervention/Exposure
555 | RBR-5hvgtky, . Effectiveness of nutritional intervention to management Systemic Arterial Hypertension in Primary Health Care. 2021. | Publication Status
556 | Recio-Rodríguez, JI, Rodriguez-Sanchez, E, Martin-Cantera, C, Martinez-Vizcaino, V, Arietaleanizbeaskoa, MS, Gonzalez-Viejo, N, Menendez-Suarez, M, Gómez-Marcos, MA, Garcia-Ortiz, L. Combined use of a healthy lifestyle smartphone application and usual primary care counseling to improve arterial stiffness, blood pressure and wave reflections: a Randomized Controlled Trial (EVIDENT II Study). Hypertension Research. 2019. 42:852–862. doi:10.1038/s41440-018-0182-6 | Intervention/Exposure
557 | Reddy, NehaK, Kaushal, Vaidehi, Kanaya, AlkaM, Kandula, NamrathaR, Gujral, UnjaliP, Shah, NilayS. Cardiovascular risk factor profiles in North and South Indian and Pakistani Americans: The MASALA Study. 2022. 244:14–18. doi:10.1016/j.ahj.2021.10.115 | Study Design
558 | Reyes-López, MA, González-Leyva, CP, Rodríguez-Cano, AM, Rodríguez-Hernández, C, Colin-Ramírez, E, Estrada-Gutierrez, G, Muñoz-Manrique, CG, Perichart-Perera, O. Diet quality is associated with a high newborn size and reduction in the risk of low birth weight and small for gestational age in a group of mexican pregnant women: An observational study. Nutrients. 2021. 13. | Confounders
559 | Ribas SA, Paravidino VB, Brandão JM, Santana da Silva LC. The Cardiovascular Health Integrated Lifestyle Diet (CHILD) Lowers LDL-Cholesterol Levels in Brazilian Dyslipidemic Pediatric Patients. 41. | Study Design; Intervention/Exposure
560 | Ribo-Coll, M, Casas, R, Roth, I, Estruch, R. The relationship between consumption of fermented alcoholic beverages, eating patterns ans anthropometric parameters in elderly patients at high cardiovascular risk. Proceedings of the Nutrition Society. 2020. 79. doi:10.1017/S0029665120003729 | Outcome; Publication Status
561 | Richardson LA, Basu A, Chien LC, Alman AC, Snell-Bergeon JK. Longitudinal associations of healthy dietary pattern scores with coronary artery calcification and pericardial adiposity in US adults with and without type 1 diabetes. | Outcome
562 | Rich-Edwards, JW, Stuart, JJ, Skurnik, G, Roche, AT, Tsigas, E, Fitzmaurice, GM, Wilkins-Haug, LE, Levkoff, SE, Seely, EW. Randomized Trial to Reduce Cardiovascular Risk in Women with Recent Preeclampsia. J Womens Health (Larchmt). 2019. 28:1493–1504. doi:10.1089/jwh.2018.7523 | Intervention/Exposure
563 | Riemer, M, Schulze, S, Wagner, L, Richter, M, Ayerle, G, Simm, A, Seeger, S, Schwesig, R, Tchirikov, M, Seliger, G. Cardiovascular Risk Reduction in Women following Hypertensive Disorders of Pregnancy - A Prospective, Randomised, Controlled Interventional Study. Geburtshilfe und Frauenheilkunde. 2021. 81:966. | Intervention/Exposure
564 | Rinott E, Meir AY, Tsaban G, Zelicha H, Kaplan A, Knights D, Tuohy K, Scholz MU, Koren O, Stampfer MJ, Wang DD, Shai I, Youngster I. The effects of the Green-Mediterranean diet on cardiometabolic health are linked to gut microbiome modifications: a randomized controlled trial. 14. | Intervention/Exposure
565 | Riseberg, E, Lopez-Cepero, A, Mangano, KM, Tucker, KL, Mattei, J. Specific Dietary Protein Sources Are Associated with Cardiometabolic Risk Factors in the Boston Puerto Rican Health Study. Journal of the Academy of Nutrition and Dietetics. 2022. 122:298. | Intervention/Exposure
566 | Ristić-Medić, D, Petrović, S, Takić, M, Vučić, V, Arsić, A, Rađen, S, Glibetić, M. EFFICACY OF A LIPID-LOWERING DIET ON KEY FATTY ACID RATIOS AND OMEGA-3 INDEX IN HYPERLIPIDEMIC SUBJECTS. UČINKOVITOST DIJETE ZA SNIŽAVANJE LIPIDA NA KLJUČNE OMJERE MASNIH KISELINA I OMEGA-3 INDEKS KOD OSOBA S HIPERLIPIDEMIJAMA. 2022. 61:220. | Intervention/Exposure
567 | Rock, CL, Zunshine, E, Nguyen, HT, Perez, AO, Zoumas, C, Pakiz, B, White, MM. Effects of pistachio consumption in a behavioral weight loss intervention on weight change, cardiometabolic factors, and dietary intake. Nutrients. 2020. 12:1–14. doi:10.3390/nu12072155 | Intervention/Exposure; Comparator
568 | Rodriguez, MA, Friedberg, JP, DiGiovanni, A, Wang, B, Wylie-Rosett, J, Hyoung, S, Natarajan, S. A Tailored Behavioral Intervention to Promote Adherence to the DASH Diet. American journal of health behavior. 2019. 43:659–670. doi:10.5993/AJHB.43.4.1 | Intervention/Exposure
569 | Rodríguez-Martín, C, Garcia-Ortiz, L, Rodriguez-Sanchez, E, Martin-Cantera, C, Soriano-Cano, A, Arietaleanizbeaskoa, MS, Magdalena-Belio, JF, Menendez-Suarez, M, Maderuelo-Fernandez, JA, Lugones-Sanchez, C, Gómez-Marcos, MA, Recio-Rodríguez, JI. The relationship of the atlantic diet with cardiovascular risk factors and markers of arterial stiffness in adults without cardiovascular disease. Nutrients. 2019. 11. doi:10.3390/nu11040742 | Study Design
570 | Röhling, M, Kempf, K, Banzer, W, Berg, A, Braumann, KM, Tan, S, Halle, M, McCarthy, D, Pinget, M, Predel, HG, Scholze, J, Toplak, H, Martin, S. Prediabetes conversion to normoglycemia is superior adding a low-carbohydrate and energy deficit formula diet to lifestyle intervention—a 12-month subanalysis of the acoorh trial. Nutrients. 2020. 12:1–13. doi:10.3390/nu12072022 | Intervention/Exposure
571 | Romanidou, M, Tripsianis, G, Hershey, MS, Sotos-Prieto, M, Christophi, C, Moffatt, S, Constantinidis, TC, Kales, SN. Association of the Modified Mediterranean Diet Score (mMDS) with Anthropometric and Biochemical Indices in US Career Firefighters. Nutrients. 2020. 12. doi:10.3390/nu12123693 | Study Design
572 | Ronca A, Pellegrini N, Pagliai G, Dinu M, Manfredini M, Incerti M, Favari E, Sofi F. Effects of a dietary intervention with Mediterranean vs lacto-ovo vegetarian diets on HDL function: Results from the CARDIVEG study. | Intervention/Exposure
573 | Roncero-Ramos, I, Alcala-Diaz, JF, Rangel-Zuniga, OA, Gomez-Delgado, F, Jimenez-Lucena, R, Garcia-Rios, A, Vals-Delgado, C, Romero-Baldonado, C, Luque, RM, Ordovas, JM, Perez-Martinez, P, Camargo, A, Lopez-Miranda, J. Prediabetes diagnosis criteria, type 2 diabetes risk and dietary modulation: The CORDIOPREV study. Clin Nutr. 2020. 39:492–500. doi:10.1016/j.clnu.2019.02.027 | Health Status
574 | Rosenberg K. Mediterranean Diet Superior to Low-Fat Diet for CVD Prevention. 122. | Publication Status
575 | Rosi, A, Tesan, M, Cremonini, A, Biasini, B, Bicchieri, L, Cossu, M, Brighenti, F, Dall’Aglio, E, Scazzina, F. Body weight of individuals with obesity decreases after a 6-month high pasta or low pasta Mediterranean diet weight-loss intervention. Nutrition, Metabolism and Cardiovascular Diseases. 2020. 30:984–995. doi:10.1016/j.numecd.2020.02.013 | Intervention/Exposure; Comparator
576 | Rostgaard-Hansen AL, Lau CJ, Halkjær J, Olsen A, Toft U. An updated validation of the Dietary Quality Score: associations with risk factors for cardiometabolic diseases in a Danish population. | Study Design
577 | Ruiz-Estigarribia, L, Martínez-González, Á M, Díaz-Gutiérrez, J, Gea, A, Rico-Campà, A, Bes-Rastrollo, M. Lifestyle-Related Factors and Total Mortality in a Mediterranean Prospective Cohort. American Journal of Preventive Medicine. 2020. 59:e59-e67. doi:10.1016/j.amepre.2020.01.032 | Outcome
578 | Rydhög, B, Granfeldt, Y, Frassetto, L, Fontes-Villalba, M, Carrera-Bastos, P, Jönsson, T. Assessing compliance with Paleolithic diet by calculating Paleolithic Diet Fraction as the fraction of intake from Paleolithic food groups. Clinical Nutrition Experimental. 2019. 25:29–35. doi:10.1016/j.yclnex.2019.03.002 | Health Status; Outcome
579 | Saeedi, P, Haszard, J, Stoner, L, Skeaff, S, Black, KE, Davison, B, Harrex, H, Meredith-Jones, K, Quigg, R, Wong, JE, Skidmore, PML. Relationships between Dietary Patterns and Indices of Arterial Stiffness and Central Arterial Wave Reflection in 9–11-Year-Old Children. Children (Basel). 2020. 7. doi:10.3390/children7060066 | Study Design
580 | Saha, S, Nordstrom, J, Gerdtham, UG, Mattisson, I, Nilsson, PM, Scarborough, P. Prevention of cardiovascular disease and cancer mortality by achieving healthy dietary goals for the swedish population: A macro-simulation modelling study. International Journal of Environmental Research and Public Health. 2019. 16. doi:10.3390/ijerph16050890 | Study Design
581 | Saha, S, Nordström, J, Mattisson, I, Nilsson, PM, Gerdtham, UG. Modelling the effect of compliance with Nordic nutrition recommendations on cardiovascular disease and cancer mortality in the Nordic countries. Nutrients. 2019. 11. doi:10.3390/nu11061434 | Study Design
582 | Said, Mohamed Ahmed, Abdelmoneem, Mohamed, Alibrahim, Mohamed Chaab, Elsebee, Moustafa Ahmed, Kotb, Ahmed Abdel Hamed. Effects of diet versus diet plus aerobic and resistance exercise on metabolic syndrome in obese young men. Journal of Exercise Science & Fitness. 2020. 18:101–108. doi:10.1016/j.jesf.2020.03.002 | Intervention/Exposure; Comparator
583 | Sajjanar, DS, Nimbal, P. Association between dietary inflammatory index and metabolic syndrome: A hospital-based study. Journal of Krishna Institute of Medical Sciences University. 2019. 8:20–29. | Study Design
584 | Salas Salvado, J. Primary prevention of cardiovascular disease with Mediterranean diet: PREDIMED studies. Obesity facts. 2021. 14:2–3. doi:10.1159/000515911 | Publication Status
585 | Salas-Salvadó, J, Díaz-López, A, Ruiz-Canela, M, Basora, J, Fitó, M, Corella, D, Serra-Majem, L, Wärnberg, J, Romaguera, D, Estruch, R, Vidal, J, Alfredo Martínez, J, Arós, F, Vázquez, C, Ros, E, Vioque, J, López-Miranda, J, Bueno-Cavanillas, A, Tur, JA, Tinahones, FJ, Martín, V, Lapetra, J, Pintó, X, Daimiel, L, Delgado-Rodríguez, M, Matía, P, Gómez-Gracia, E, Díez-Espino, J, Babio, N, Castañer, O, Sorlí, JV, Fiol, M, Zulet, Á M, Bulló, M, Goday, A, Martínez-González, Á M. Effect of a lifestyle intervention program with energy-restricted Mediterranean diet and exercise on weight loss and cardiovascular risk factors: One-year results of the PREDIMED-Plus trial. Diabetes Care. 2019. 42:777–788. doi:10.2337/dc18-0836 | Comparator
586 | Salvador, AM, García-Maldonado, E, Gallego-Narbón, A, Zapatera, B, Vaquero, MP. Fatty acid profile and cardiometabolic markers in relation with diet type and omega-3 supplementation in Spanish vegetarians. Nutrients. 2019. 11. doi:10.3390/nu11071659 | Study Design
587 | Samuel-Hodge CD, Ziya Gizlice, Allgood SD, Bunton AJ, Erskine A, Leeman J, Cykert S. A Hybrid Implementation-Effectiveness Study of a Community Health Worker-Delivered Intervention to Reduce Cardiovascular Disease Risk in a Rural, Underserved Non-Hispanic Black Population: The CHANGE Study. | Study Design
588 | Sánchez-Escudero V, García Lacalle C, González Vergaz A, Mateo LR, Marqués Cabrero A. The triglyceride/glucose index as an insulin resistance marker in the pediatric population and its relation to eating habits and physical activity. 68. | Study Design; Intervention/Exposure
589 | Sanllorente A, Soria-Florido MT, Castañer O, Lassale C, Salas-Salvadó J, Martínez-González MÁ, Subirana I, Ros E, Corella D, Estruch R, Tinahones FJ, Hernáez Á, Fitó M. A lifestyle intervention with an energy-restricted Mediterranean diet and physical activity enhances HDL function: a substudy of the PREDIMED-Plus randomized controlled trial. | Intervention/Exposure; Comparator
590 | Santiago, S, Zazpe, I, Fernandez-Lazaro, CI, de la O, V, Bes-Rastrollo, M, Martínez-González, Á M. Macronutrient quality and all-cause mortality in the sun cohort. Nutrients. 2021. 13:1–17. doi:10.3390/nu13030972 | Intervention/Exposure
591 | Santos, Aseac, Rodrigues, Apds, Rosa, LPS, Noll, M, Silveira, EA. Traditional Brazilian Diet and Olive Oil Reduce Cardiometabolic Risk Factors in Severely Obese Individuals: A Randomized Trial. Nutrients. 2020. 12. doi:10.3390/nu12051413 | Intervention/Exposure; Comparator
592 | Santos, KD, Moreira, TM, Belfort, GP, Silva, CFMD, Padilha, PC, Barros, DC, Saunders, C. Adaptation of DASH diet (Dietary Approach to Stop Hypertension) for postpartum nutritional care at primary healthcare. Revista brasileira de epidemiologia = Brazilian journal of epidemiology. 2019. 22:e190035. doi:10.1590/1980-549720190035 | Outcome; Publication Status
593 | Šarac, J, Auguštin, DH, Lovrić, M, Stryeck, S, Šunić, I, Novokmet, N, Missoni, S. A generation shift in mediterranean diet adherence and its association with biological markers and health in dalmatia, Croatia. Nutrients. 2021. 13. | Study Design
594 | Saslow LR, Jones LM, Sen A, Wolfson JA, Diez HL, O’Brien A, Leung CW, Bayandorian H, Daubenmier J, Missel AL, Richardson C. Comparing Very Low-Carbohydrate vs DASH Diets for Overweight or Obese Adults With Hypertension and Prediabetes or Type 2 Diabetes: A Randomized Trial. 21. | Comparator
595 | Sayón-Orea, C, Razquin, C, Bulló, M, Corella, D, Fitó, M, Romaguera, D, Vioque, J, Alonso-Gómez, ÁM, Wärnberg, J, Martínez, JA, Serra-Majem, L, Estruch, R, Tinahones, FJ, Lapetra, J, Pintó, X, Tur, JA, López-Miranda, J, Bueno-Cavanillas, A, Delgado-Rodríguez, M, Matía-Martín, P, Daimiel, L, Sánchez, VM, Vidal, J, Vázquez, C, Ros, E, Ruiz-Canela, M, Sorlí, JV, Castañer, O, Fiol, M, Navarrete-Muñoz, EM, Arós, F, Gómez-Gracia, E, Zulet, MA, Sánchez-Villegas, A, Casas, R, Bernal-López, R, Santos-Lozano, JM, Corbella, E, Bouzas, C, García-Arellano, A, Basora, J, Asensio, EM, Schröder, H, Moñino, M, García De La Hera, M, Tojal-Sierra, L, Toledo, E, Díaz-López, A, Goday, A, Salas-Salvadó, J, Martínez-González, MA. Effect of a Nutritional and Behavioral Intervention on Energy-Reduced Mediterranean Diet Adherence among Patients with Metabolic Syndrome: Interim Analysis of the PREDIMED-Plus Randomized Clinical Trial. JAMA - Journal of the American Medical Association. 2019. 322:1486–1499. doi:10.1001/jama.2019.14630 | Intervention/Exposure; Outcome
596 | Schaffer, AnnaE, D’Alessio, DavidA, Guyton, JohnR. Extreme elevations of low-density lipoprotein cholesterol with very low carbohydrate, high fat diets. Journal of Clinical Lipidology. 2021. 15:525–526. doi:10.1016/j.jacl.2021.04.010 | Study Design; Publication Status
597 | Schmidt KA, Cromer G, Burhans MS, Kuzma JN, Hagman DK, Fernando I, Murray M, Utzschneider KM, Holte S, Kraft J, Kratz M. Impact of low-fat and full-fat dairy foods on fasting lipid profile and blood pressure: exploratory endpoints of a randomized controlled trial. 114. | Intervention/Exposure
598 | Schnermann ME, Schulz CA, Herder C, Alexy U, Nöthlings U. A lifestyle pattern during adolescence is associated with cardiovascular risk markers in young adults: results from the DONALD cohort study. 10. | Intervention/Exposure
599 | Schutte, Sophie, Esser, Diederik, Siebelink, Els, Michielsen, CharlotteJR, Daanje, Monique, Matualatupauw, JuriC, Boshuizen, HendriekC, Mensink, Marco, Afman, LydiaA, team, The Wageningen Belly Fat Study. Diverging metabolic effects of 2 energy-restricted diets differing in nutrient quality: a 12-week randomized controlled trial in subjects with abdominal obesity. American Journal of Clinical Nutrition. 2022. 116:132–150. doi:10.1093/ajcn/nqac025 | Intervention/Exposure
600 | Schwingshackl, L, Knüppel, S, Michels, N, Schwedhelm, C, Hoffmann, G, Iqbal, K, De Henauw, S, Boeing, H, Devleesschauwer, B. Intake of 12 food groups and disability-adjusted life years from coronary heart disease, stroke, type 2 diabetes, and colorectal cancer in 16 European countries. European Journal of Epidemiology. 2019. 34:765–775. doi:10.1007/s10654-019-00523-4 | Intervention/Exposure
601 | Seangpraw, K, Auttama, N, Tonchoy, P, Panta, P. The effect of the behavior modification program Dietary Approaches to Stop Hypertension (DASH) on reducing the risk of hypertension among elderly patients in the rural community of Phayao, Thailand. Journal of Multidisciplinary Healthcare. 2019. 12:109–118. doi:10.2147/JMDH.S185569 | Intervention/Exposure
602 | Seconda, L, Baudry, J, Alles, B, Touvier, M, Hercberg, S, Pointereau, P, Lairon, D, Kesse-Guyot, E. Prospective associations between sustainable dietary pattern assessed with the Sustainable Diet Index (SDI) and risk of cancer and cardiovascular diseases in the French NutriNet-Sante cohort. Eur J Epidemiol. 2020. 35:471–481. doi:10.1007/s10654-020-00619-2 | Intervention/Exposure
603 | Seguin, R, Folta, S, Marshall, G, Graham, M, Strogatz, DS. The effect of a community-based healthy lifestyle behavior change program on simple 7 score among rural women. Circulation. 2019. 139. doi:10.1161/circ.139.suppl_1.P144 | Publication Status; Comparator
604 | Seguin-Fowler, RA, Eldridge, GD, Rethorst, CD, Graham, ML, Demment, M, Strogatz, D, Folta, SC, Maddock, JE, Nelson, ME, Ha, S. Improvements and Maintenance of Clinical and Functional Measures among Rural Women: Strong Hearts, Healthy Communities-2. 0 Cluster Randomized Trial. Circulation: Cardiovascular Quality and Outcomes. 2022. 15:E009333. | Intervention/Exposure
605 | Seguin-Fowler, RA, Strogatz, D, Graham, ML, Eldridge, GD, Marshall, GA, Folta, SC, Pullyblank, K, Nelson, ME, Paul, L. The Strong Hearts, Healthy Communities Program 2.0: An RCT Examining Effects on Simple 7. Am J Prev Med. 2020. 59:32–40. doi:10.1016/j.amepre.2020.01.027 | Intervention/Exposure
606 | Seo, AR, Hwang, TY. Relationship between Dietary Patterns and Cardiovascular Disease Risk in Korean Older Adults. Int J Environ Res Public Health. 2021. 18. doi:10.3390/ijerph18073703 | Study Design
607 | Seremet Kurklu, N, Karatas Torun, N, Ozen Kucukcetin, I, Akyol, A. Is there a relationship between the dietary inflammatory index and metabolic syndrome among adolescents?. J Pediatr Endocrinol Metab. 2020. 33:495–502. doi:10.1515/jpem-2019-0409 | Study Design
608 | Serra, MC, Beavers, DP, Henderson, RM, Kelleher, JL, Kiel, JR, Beavers, KM. Effects of a hypocaloric, nutritionally complete, higher protein meal plan on regional body fat and cardiometabolic biomarkers in older adults with obesity. Annals of Nutrition and Metabolism. 2019. 74:149–155. doi:10.1159/000497066 | Intervention/Exposure; Outcome
609 | Setayesh, L, Ebrahimi, R, Pooyan, S, Yarizadeh, H, Rashidbeygi, E, Badrooj, N, Imani, H, Mirzaei, K. The possible mediatory role of adipokines in the association between low carbohydrate diet and depressive symptoms among overweight and obese women. PLoS ONE. 2021. 16. | Study Design; Intervention/Exposure; Outcome
610 | Setiono, FJ, Jock, B, Trude, A, Wensel, CR, Poirier, L, Pardilla, M, Gittelsohn, J. Associations between Food Consumption Patterns and Chronic Diseases and Self-Reported Morbidities in 6 American Indian Communities. Current Developments in Nutrition. 2019. 3:69–80. doi:10.1093/cdn/nzz067 | Study Design; Outcome
611 | Setyopranoto, I, Bayuangga, HF, Panggabean, AS, Alifaningdyah, S, Lazuardi, L, Dewi, FST, Malueka, RG. Prevalence of stroke and associated risk factors in sleman district of Yogyakarta Special Region, Indonesia. Stroke Research and Treatment. 2019. 2019. doi:10.1155/2019/2642458 | Outcome; Country
612 | Seyedi, SHS, Mottaghi, A, Mirmiran, P, Hedayati, M, Azizi, F. The relationship between dietary patterns and lipoprotein-associated phospholipase A2 levels in adults with cardiovascular risk factors: Tehran Lipid and Glucose Study. J Res Med Sci. 2020. 25:3. doi:10.4103/jrms.JRMS_256_19 | Outcome
613 | Sezaki, A, Imai, T, Miyamoto, K, Kawase, F, Shimokata, H. Mediterranean diet score and incidence of IHD: a global comparative study. Public health nutrition. 2019. 22:1444–1450. doi:10.1017/S1368980018003877 | Study Design
614 | Sezaki, A, Imai, T, Miyamoto, K, Kawase, F, Shirai, Y, Abe, C, Sanada, M, Inden, A, Kato, T, Suzuki, N, Shimokata, H. Global relationship between Mediterranean diet and the incidence and mortality of ischaemic heart disease. Eur J Public Health. 2021. 31:608–612. doi:10.1093/eurpub/ckab008 | Study Design
615 | Shah RV, Steffen LM, Nayor M, Reis JP, Jacobs DR, Allen NB, Lloyd-Jones D, Meyer K, Cole J, Piaggi P, Vasan RS, Clish CB, Murthy VL. Dietary metabolic signatures and cardiometabolic risk. | Intervention/Exposure
616 | Shamsi, SA, Salehzadeh, M, Ghavami, H, Aghaji Asl, RG, Vatani, KK. Impact of lifestyle interventions on reducing dietary sodium intake and blood pressure in patients with hypertension: A randomized controlled trial. Turk Kardiyol Dern Ars. 2021. 49:143–150. doi:10.5543/tkda.2021.81669 | Intervention/Exposure
617 | Shang X, Li Y, Xu H, Zhang Q, Liu A, Du S, Guo H, Ma G. Leading dietary determinants identified using machine learning techniques and a healthy diet score for changes in cardiometabolic risk factors in children: a longitudinal analysis. 19. | Country
618 | Shang, X, Li, Y, Xu, H, Zhang, Q, Liu, A, Ma, G. The Clustering of Low Diet Quality, Low Physical Fitness, and Unhealthy Sleep Pattern and Its Association with Changes in Cardiometabolic Risk Factors in Children. Nutrients. 2020. 12. doi:10.3390/nu12020591 | Outcome; Country
619 | Sharma, N, Raj, J, Seehra, N. Lipid profile evaluation in second and third trimester of pregnancy and fetomaternal outcome. International Journal of Pharmaceutical Sciences Review and Research. 2021. 69:112–117. doi:10.47583/ijpsrr.2021.v69i01.017 | Country
620 | Shi, J, Fang, H, Cheng, X, Guo, Q, Ju, L, Piao, W, Xu, X, Yu, D, Zhao, L, He, L. Nutrient Patterns and Its Association and Metabolic Syndrome among Chinese Children and Adolescents Aged 7?17. Nutrients. 2023. 15. | Study Design; Intervention/Exposure
621 | Shi, J, Fang, H, Guo, Q, Yu, D, Ju, L, Cheng, X, Piao, W, Xu, X, Li, Z, Mu, D, Zhao, L, He, L. Association of Dietary Patterns with Metabolic Syndrome in Chinese Children and Adolescents Aged 7–17: The China National Nutrition and Health Surveillance of Children and Lactating Mothers in 2016–2017. Nutrients. 2022. 14. | Study Design
622 | Shi, Z, Ganji, V. Dietary patterns and cardiovascular disease risk among Chinese adults: a prospective cohort study. Eur J Clin Nutr. 2020. 74:1725–1735. doi:10.1038/s41430-020-0668-6 | Country
623 | Shih, CW, Hauser, ME, Aronica, L, Rigdon, J, Gardner, CD. Changes in blood lipid concentrations associated with changes in intake of dietary saturated fat in the context of a healthy low-carbohydrate weight-loss diet: A secondary analysis of the Diet Intervention Examining the Factors Interacting with Treatment Success (DIETFITS) trial. American Journal of Clinical Nutrition. 2019. 109:433–441. doi:10.1093/ajcn/nqy305 | Intervention/Exposure
624 | Shim SY, Kim HC, Shim JS. Consumption of Ultra-Processed Food and Blood Pressure in Korean Adults. | Study Design
625 | Shim, JS, Jung, SJ, Kim, HC. Self-reported diet management, dietary quality, and blood pressure control in Korean adults with hypertension. Clin Hypertens. 2019. 25:24. doi:10.1186/s40885-019-0130-z | Study Design
626 | Shim, JS, Oh, K, Jung, SJ, Kim, HC. Self-Reported Diet Management and Adherence to Dietary Guidelines in Korean Adults with Hypertension. Korean Circ J. 2020. 50:432–440. doi:10.4070/kcj.2019.0230 | Study Design
627 | Shin N, Kim J. Association between different types of plant-based diet and dyslipidaemia in Korean adults. 128. | Study Design
628 | Shin, J, Ham, D, Shin, S, Choi, SK, Paik, HY, Joung, H. Effects of lifestyle-related factors on ischemic heart disease according to body mass index and fasting blood glucose levels in Korean adults. PLoS ONE. 2019. 14. doi:10.1371/journal.pone.0216534 | Intervention/Exposure
629 | Shin, N, Kim, J. Association between different types of plant-based diet and dyslipidemia in Korean adults. British Journal of Nutrition. 2021. | Study Design
630 | Shivakoti R, Biggs ML, Djoussé L, Durda PJ, Kizer JR, Psaty B, Reiner AP, Tracy RP, Siscovick D, Mukamal KJ. Intake and Sources of Dietary Fiber, Inflammation, and Cardiovascular Disease in Older US Adults. 5. | Intervention/Exposure
631 | Singh, S, Eastwood, CA. Nurses’ awareness of diverse healthy diets may increase patients’ adherence improving cardiovascular disease risk management. Evid Based Nurs. 2020. doi:10.1136/ebnurs-2020-103329 | Study Design; Publication Status
632 | Siregar, DAS, Rianda, D, Irwinda, R, Dwi Utami, A, Hanifa, H, Shankar, AH, Agustina, R. Associations between diet quality, blood pressure, and glucose levels among pregnant women in the Asian megacity of Jakarta. PLoS One. 2020. 15:e0242150. doi:10.1371/journal.pone.0242150 | Study Design
633 | Siritharan SS, Henry A, Gow ML, Roberts LM, Yao A, Ojurovic M, O’Sullivan AJ. Maternal macro- and micronutrient intake six months after hypertensive versus normotensive pregnancy: is poor diet quality contributing to future cardiometabolic disease risk?. 23. | Study Design; Intervention/Exposure
634 | Sisa, I, Abeyá-Gilardon, E, Fisberg, RM, Jackson, MD, Mangialavori, GL, Sichieri, R, Cudhea, F, Bannuru, RR, Ruthazer, R, Mozaffarian, D, Singh, GM. Impact of diet on CVD and diabetes mortality in Latin America and the Caribbean: a comparative risk assessment analysis. Public health nutrition. 2021. 24:2577. | Study Design
635 | Skelly, LE, Barbour-Tuck, EN, Kurgan, N, Calleja, M, Klentrou, P, Falk, B, Josse, AR. Neutral Effect of Increased Dairy Product Intake, as Part of a Lifestyle Modification Program, on Cardiometabolic Health in Adolescent Girls With Overweight/Obesity: A Secondary Analysis From a Randomized Controlled Trial. Front Nutr. 2021. 8:673589. doi:10.3389/fnut.2021.673589 | Intervention/Exposure
636 | Skrypnik, K, Bogdanski, P, Kubasik, M, Wawrzyniak, N, Markuszewski, L, Suliburska, J. The influence of dietary patterns on arterial stiffness, lipid metabolism, and liver and renal function in the population of Greater Poland. Acta scientiarum polonorum. Technologia alimentaria. 2020. 19:301. | Study Design; Intervention/Exposure
637 | Smiljanec, K, Mbakwe, AU, Ramos-Gonzalez, M, Mesbah, C, Lennon, SL. Associations of Ultra-Processed and Unprocessed/Minimally Processed Food Consumption with Peripheral and Central Hemodynamics, and Arterial Stiffness in Young Healthy Adults. Nutrients. 2020. 12. doi:10.3390/nu12113229 | Study Design
638 | Smith, PJ, Sherwood, A, Hinderliter, AL, Mabe, S, Tyson, C, Avorgbedor, F, Watkins, LL, Lin, P-H, Kraus, WE, Blumenthal, JA. Cerebrovascular Function, Vascular Risk, and Lifestyle Patterns in Resistant Hypertension. Journal of Alzheimer’s disease : JAD. 2022. | Study Design; Intervention/Exposure; Outcome
639 | Song Y, Chang Z, Jia L, Song W, Wang H, Dong Q, Dou K. Better adherence to the MIND diet is associated with lower risk of all-cause death and cardiovascular death in patients with atherosclerotic cardiovascular disease or stroke: a cohort study from NHANES analysis. | Health Status
640 | Song Z, Yang R, Wang W, Huang N, Zhuang Z, Han Y, Qi L, Xu M, Tang YD, Huang T. Association of healthy lifestyle including a healthy sleep pattern with incident type 2 diabetes mellitus among individuals with hypertension. 20. | Intervention/Exposure; Outcome
641 | Song, S, Lee, K, Park, S, Shin, N, Kim, H, Kim, J. Association between unhealthful plant-based diets and possible risk of dyslipidemia. Nutrients. 2021. 13. | Study Design
642 | Song, S, Lee, JE. Dietary patterns related to triglyceride and high-density lipoprotein cholesterol and the incidence of type 2 diabetes in Korean men and women. Nutrients. 2019. 11. doi:10.3390/nu11010008 | Outcome
643 | Soria-Contreras, DC, Rifas-Shiman, SL, Aris, IM, Perng, W, Switkowski, KM, Tellez-Rojo, MM, Trejo-Valdivia, B, Lopez-Ridaura, R, Oken, E. Weight Trajectories After Delivery are Associated with Adiposity and Cardiometabolic Markers at 3 Years Postpartum Among Women in Project Viva. J Nutr. 2020. 150:1889–1898. doi:10.1093/jn/nxaa104 | Outcome; Comparator
644 | Soria-Florido, MT, Castaner, O, Lassale, C, Estruch, R, Salas-Salvado, J, Martinez-Gonzalez, MA, Corella, D, Ros, E, Aros, F, Elosua, R, Lapetra, J, Fiol, M, Alonso-Gomez, A, Gomez-Gracia, E, Serra-Majem, L, Pinto, X, Bullo, M, Ruiz-Canela, M, Sorli, JV, Hernaez, A, Fito, M. Dysfunctional High-Density Lipoproteins Are Associated With a Greater Incidence of Acute Coronary Syndrome in a Population at High Cardiovascular Risk: A Nested Case-Control Study. Circulation. 2020. 141:444–453. doi:10.1161/CIRCULATIONAHA.119.041658 | Study Design; Intervention/Exposure
645 | Sotos-Prieto M, Ortolá R, Ruiz-Canela M, Garcia-Esquinas E, Martínez-Gómez D, Lopez-Garcia E, Martínez-González MÁ, Rodriguez-Artalejo F. Association between the Mediterranean lifestyle, metabolic syndrome and mortality: a whole-country cohort in Spain. 20. | Intervention/Exposure; Outcome
646 | Sotos-Prieto, M, Zhao, S, Kline, D, Brock, G, Gooding, H, Mattei, J, Rodriguez-Artalejo, F, Min, Y-I, Rimm, EB, Tucker, KL, Joseph, JJ. Application of a lifestyle-based score to predict cardiovascular risk in African Americans: The Jackson heart study. Journal of Clinical Medicine. 2021. 10. | Intervention/Exposure
647 | Sotos-Prieto, M, Ruiz-Canela, M, Song, Y, Christophi, C, Mofatt, S, Rodriguez-Artalejo, F, Kales, SN. The Effects of a Mediterranean Diet Intervention on Targeted Plasma Metabolic Biomarkers among US Firefighters: A Pilot Cluster-Randomized Trial. Nutrients. 2020. 12. doi:10.3390/nu12123610 | Intervention/Exposure
648 | Spence, David J, Tangney, Christy. Lower risk of stroke with a vegetarian diet. Neurology. 2020. 94:463–464. doi:10.1212/WNL.0000000000009092 | Publication Status
649 | Stanaway, FF, Ribeiro, RV, Khalatbari-Soltani, S, Cvejic, E, Blyth, FM, Naganathan, V, Handelsman, DJ, Le Couteur, DG, Simpson, SJ, Waite, LM, Cumming, RG, Hirani, V. Diet quality in an ethnically diverse population of older men in Australia. Eur J Clin Nutr. 2021. doi:10.1038/s41430-021-00893-7 | Outcome
650 | Steinberg, D, Kay, M, Burroughs, J, Svetkey, LP, Bennett, GG. The Effect of a Digital Behavioral Weight Loss Intervention on Adherence to the Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern in Medically Vulnerable Primary Care Patients: Results from a Randomized Controlled Trial. Journal of the Academy of Nutrition and Dietetics. 2019. 119:574–584. doi:10.1016/j.jand.2018.12.011 | Confounders
651 | Steinberg, DM, Kay, MC, Svetkey, LP, Askew, S, Christy, J, Burroughs, J, Ahmed, H, Bennett, GG. Feasibility of a Digital Health Intervention to Improve Diet Quality Among Women With High Blood Pressure: Randomized Controlled Feasibility Trial. JMIR Mhealth Uhealth. 2020. 8:e17536. doi:10.2196/17536 | Intervention/Exposure; Comparator
652 | Sterling, SR, Bowen, S-A. Effect of a Plant-based Intervention Among Black Individuals in the Deep South: A Pilot Study. Journal of nutrition education and behavior. 2022. | Study Design; Comparator
653 | Strączek K, Horodnicka-Józwa A, Szmit-Domagalska J, Jackowski T, Safranow K, Petriczko E, Walczak M. Familial dietary intervention in children with excess body weight and its impact on eating habits, anthropometric and biochemical parameters. 13. | Intervention/Exposure
654 | Subhan, FB, Chan, CB. Diet quality and risk factors for cardiovascular disease among South Asians in Alberta. Applied physiology, nutrition, and metabolism = Physiologie appliquee, nutrition et metabolisme. 2019. 44:886–893. doi:10.1139/apnm-2018-0868 | Study Design
655 | Suliga, E, Brola, W, Sobaś, K, Cieśla, E, Jasińska, E, Gołuch, K, Głuszek, S. Dietary Patterns and Metabolic Disorders in Polish Adults with Multiple Sclerosis. Nutrients. 2022. 14. | Health Status
656 | Sullivan, VK, Appel, LJ, Seegmiller, JC, McClure, ST, Rebholz, CM. A Low-Sodium DASH Dietary Pattern Affects Serum Markers of Inflammation and Mineral Metabolism in Adults with Elevated Blood Pressure. The Journal of nutrition. 2021. doi:10.1093/jn/nxab236 | Study Duration
657 | Sullivan, VK, Appel, LJ, Seegmiller, JC, Rebholz, CM. Effect of the dash-sodium diet on serum biomarkers of inflammation and mineral metabolism. Circulation. 2021. 143. doi:10.1161/circ.143.suppl_1.MP01 | Study Duration; Publication Status
658 | Sun Y, Liu B, Snetselaar LG, Wallace RB, Shadyab AH, Kroenke CH, Haring B, Howard BV, Shikany JM, Valdiviezo C, Bao W. Association of Major Dietary Protein Sources With All-Cause and Cause-Specific Mortality: Prospective Cohort Study. 10. | Intervention/Exposure
659 | Sun, J, Buys, NJ, Hills, AP. Dietary pattern and its association with the prevalence of obesity, hypertension and other cardiovascular risk factors among Chinese older adults. International Journal of Environmental Research and Public Health. 2014. 11:3956. | Study Design
660 | Sundfør, TM, Svendsen, M, Heggen, E, Dushanov, S, Klemsdal, TO, Tonstad, S. BMI modifies the effect of dietary fat on atherogenic lipids: A randomized clinical trial. American Journal of Clinical Nutrition. 2019. 110:832–841. doi:10.1093/ajcn/nqz113 | Intervention/Exposure; Study Duration
661 | Syrén, M-L, Turolo, S, de Marco, EA, De Cosmi, V, Risé, P, Marangoni, F, Minoli, DG, Manzoni, G, Agostoni, C. Whole blood fatty acid profile of young subjects and adherence to the Mediterranean diet: an observational cohort study. Lipids in health and disease. 2022. 21:23. | Intervention/Exposure; Outcome
662 | Taba, N, Valge, H-K, Metspalu, A, Esko, T, Wilson, JF, Fischer, K, Pirastu, N. Mendelian Randomization Identifies the Potential Causal Impact of Dietary Patterns on Circulating Blood Metabolites. Frontiers in Genetics. 2021. 12. | Intervention/Exposure
663 | Tan YWB, Lau JH, AshaRani PV, Roystonn K, Devi F, Lee YY, Whitton C, Wang P, Shafie S, Chang S, Jeyagurunathan A, Chua BY, Abdin E, Sum CF, Lee ES, Subramaniam M. Dietary patterns of persons with chronic conditions within a multi-ethnic population: results from the nationwide Knowledge, Attitudes and Practices survey on diabetes in Singapore. 80. | Study Design
664 | TCTR20210428005, . Effect of Lifestyle Modification on Metabolic factors, Musculoskeletal Health, Reproductive Hormone and Quality of life in Older People Who have Diabetes, Hypertension or Dyslipidemia. 2021. | Publication Status
665 | Temporelli PL. Cardiovascular prevention: Mediterranean or low-fat diet?. 25. | Study Design
666 | Terschüren, C, Damerau, L, Petersen, EL, Harth, V, Augustin, M, Zyriax, B-C. Association of dietary pattern, lifestyle and chronotype with metabolic syndrome in elderly—lessons from the population-based hamburg city health study. International Journal of Environmental Research and Public Health. 2022. 19. | Study Design
667 | Thao U, Lajous M, Laouali N, Severi G, Boutron-Ruault MC, MacDonald CJ. Replacing processed red meat with alternative protein sources is associated with a reduced risk of hypertension and diabetes in a prospective cohort of French women. | Intervention/Exposure; Comparator
668 | Tischmann, L, Adam, TC, Mensink, RP, Joris, PJ. Longer-term soy nut consumption improves vascular function and cardiometabolic risk markers in older adults: Results of a randomized, controlled cross-over trial. Clinical Nutrition. 2022. 41:1052. | Intervention/Exposure; Comparator
669 | Tischmann, L, Drummen, M, Joris, PJ, Gatta-Cherifi, B, Raben, A, Fogelholm, M, Matias, I, Cota, D, Mensink, RP, Westerterp-Plantenga, MS, Adam, TC. Effects of a high-protein diet on cardiometabolic health, vascular function, and endocannabinoids—a preview study. Nutrients. 2020. 12. doi:10.3390/nu12051512 | Intervention/Exposure
670 | Tisdel, DM, Gadberry, JJ, Burke, SL, Carlini, NA, Fleenor, BS, Campbell, MS. Dietary fat and alcohol in the prediction of indices of vascular health among young adults. Nutrition. 2021. 84:111120. doi:10.1016/j.nut.2020.111120 | Study Design; Intervention/Exposure; Outcome
671 | Titcomb TJ, Liu B, Wahls TL, Snetselaar LG, Shadyab AH, Tabung FK, Saquib N, Arcan C, Tinker LF, Wallace RB, Bao W. Comparison of the ketogenic ratio of macronutrients with the low-carbohydrate diet score and their association with risk of type 2 diabetes in postmenopausal women: A secondary analysis of the women’s health initiative. | Intervention/Exposure; Outcome
672 | Toh, DWK, Xia, X, Sutanto, CN, Low, JHM, Poh, KK, Wang, J-W, Foo, RS-Y, Kim, JE. Enhancing the cardiovascular protective effects of a healthy dietary pattern with wolfberry (Lycium barbarum): A randomized controlled trial. American Journal of Clinical Nutrition. 2021. 114:80. | Intervention/Exposure
673 | Tosi M, Matelloni IA, Mancini M, Andreassi A, Scopari A, Rossi A, Verduci E, Berra C, Manfrini R, Banderali G, Pecori Giraldi F, Folli F. Multiple beneficial effects of 1-year nutritional-behavioral intervention on anthropometric and metabolic parameters in overweight and obese boys. | Intervention/Exposure; Comparator
674 | Tripp, ML, Dahlberg, CJ, Eliason, S, Lamb, JJ, Ou, JJ, Gao, W, Bhandari, J, Graham, D, Dudleenamjil, E, Babish, JG. A Low-Glycemic, Mediterranean Diet and Lifestyle Modification Program with Targeted Nutraceuticals Reduces Body Weight, Improves Cardiometabolic Variables and Longevity Biomarkers in Overweight Subjects: A 13-Week Observational Trial. Journal of Medicinal Food. 2019. 22:479–489. doi:10.1089/jmf.2018.0063 | Study Design
675 | Tsaban, G, Yaskolka Meir, A, Zelicha, H, Rinott, E, Kaplan, A, Shalev, A, Katz, A, Brikner, D, Blüher, M, Ceglarek, U, Stumvoll, M, Stampfer, MJ, Shai, I. Diet-induced fasting ghrelin elevation reflects the recovery of insulin sensitivity and visceral adiposity regression. The Journal of clinical endocrinology and metabolism. 2021. | Comparator
676 | Tsaban, G, Yaskolka Meir, A, Rinott, E, Zelicha, H, Kaplan, A, Shalev, A, Katz, A, Rudich, A, Tirosh, A, Shelef, I, Youngster, I, Lebovitz, S, Israeli, N, Shabat, M, Brikner, D, Pupkin, E, Stumvoll, M, Thiery, J, Ceglarek, U, Heiker, JT, Körner, A, Landgraf, K, Von Bergen, M, Blüher, M, Stampfer, MJ, Shai, I. The effect of green Mediterranean diet on cardiometabolic risk; A randomised controlled trial. Heart. 2020. doi:10.1136/heartjnl-2020-317802 | Comparator
677 | Tsai MC, Yeh TL, Hsu HY, Hsu LY, Lee CC, Tseng PJ, Chien KL. Comparison of four healthy lifestyle scores for predicting cardiovascular events in a national cohort study. 11. | Intervention/Exposure; Country
678 | Tsoi KY, Chan RSM, Tam CHT, Li LS, Tam WH, Ma RCW. Dietary patterns of Chinese pregnant women in Hong Kong. 31. | Confounders
679 | Tsoi, KY, Chan, RSM, Li, LS, McAuliffe, FM, Hanson, MA, Tam, WH, Ma, RCW. Evaluation of dietary pattern in early pregnancy using the FIGO Nutrition Checklist compared to a food frequency questionnaire. Int J Gynaecol Obstet. 2020. 151 Suppl 1:37–44. doi:10.1002/ijgo.13324 | Outcome
680 | Tuleuova, R, Zhamaliyeva, L, Grjibovski, A. Dietary Factors and Changes in Blood Pressure in Adult Kazakhs: A 3-year Follow-Up Study. Open Access Macedonian Journal of Medical Sciences. 2022. 10:2146. | Intervention/Exposure
681 | Turner-McGrievy GM, Wilson MJ, Carswell J, Okpara N, Aydin H, Bailey S, Davey M, Hutto B, Wilcox S, Friedman DB, Sarzynski MA, Liese AD. A 12-Week Randomized Intervention Comparing the Healthy US, Mediterranean, and Vegetarian Dietary Patterns of the US Dietary Guidelines for Changes in Body Weight, Hemoglobin A1c, Blood Pressure, and Dietary Quality among African American Adults. 153. | Intervention/Exposure
682 | Turner-McGrievy, GM, Wirth, MD, Shivappa, N, Dunn, CG, Crimarco, A, Hurley, TG, West, DS, Hussey, JR, Hébert, JR. Impact of a 12-month Inflammation Management Intervention on the Dietary Inflammatory Index, inflammation, and lipids. Clinical Nutrition ESPEN. 2019. 30:42–51. doi:10.1016/j.clnesp.2019.02.008 | Study Design; Intervention/Exposure; Comparator
683 | Tuttolomondo, A, Di Raimondo, D, Casuccio, A, Velardo, M, Salamone, G, Arnao, V, Pecoraro, R, Della Corte, V, Restivo, V, Corpora, F, Maida, C, Simonetta, I, Cirrincione, A, Vassallo, V, Pinto, A. Relationship between adherence to the Mediterranean Diet, intracerebral hemorrhage, and its location. Nutrition, Metabolism and Cardiovascular Diseases. 2019. 29:1118–1125. doi:10.1016/j.numecd.2019.06.010 | Study Design; Health Status
684 | Tyson, CC, Davenport, CA, Lin, PH, Scialla, JJ, Hall, R, Diamantidis, CJ, Lunyera, J, Bhavsar, N, Rebholz, CM, Pendergast, J, Boulware, LE, Svetkey, LP. DASH diet and blood pressure among black Americans with and without CKD: The Jackson Heart Study. American Journal of Hypertension. 2019. 32:975–982. doi:10.1093/ajh/hpz090 | Study Design; Intervention/Exposure
685 | Tzelefa V, Tsirimiagkou C, Argyris A, Moschonis G, Perogiannakis G, Yannakoulia M, Sfikakis P, Protogerou AD, Karatzi K. Associations of dietary patterns with blood pressure and markers of subclinical arterial damage in adults with risk factors for CVD. 24. | Study Design
686 | Tzelefa, V, Tsirimiagkou, C, Argyris, A, Moschonis, G, Perogiannakis, G, Yannakoulia, M, Sfikakis, P, Protogerou, AD, Karatzi, K. Associations of dietary patterns with blood pressure and markers of subclinical arterial damage in adults with risk factors for cardiovascular disease. Public health nutrition. 2021. 1–25. doi:10.1017/S1368980021003499 | Study Design
687 | Tzenios, N, Lewis, ED, Crowley, DC, Chahine, M, Evans, M. Examining the Efficacy of a Very-LowCarbohydrate Ketogenic Diet on Cardiovascular Health in Adults with Mildly Elevated Low-Density Lipoprotein Cholesterol in an Open-Label Pilot Study. Metabolic Syndrome and Related Disorders. 2022. 20:94. | Study Design
688 | Uma Maheswari, S. Healthy hypertension. European Journal of Molecular and Clinical Medicine. 2020. 7:6025–6029. | Publication Status
689 | Umeki Y, Hayabuchi H, Adachi H, Ohta M. Feasibility of Low-Sodium, High-Potassium Processed Foods and Their Effect on Blood Pressure in Free-Living Japanese Men: A Randomized, Double-Blind Controlled Trial. 13. | Intervention/Exposure; Study Duration
690 | Umemoto, S, Onaka, U, Kawano, R, Kawamura, A, Motoi, S, Honda, N, Kanazashi, H, Mitarai, M, Dash Diet Study Group J. Effects of a Japanese Cuisine-Based Antihypertensive Diet and Fish Oil on Blood Pressure and Its Variability in Participants with Untreated Normal High Blood Pressure or Stage I Hypertension: A Feasibility Randomized Controlled Study. J Atheroscler Thromb. 2020. doi:10.5551/jat.57802 | Study Duration
691 | Unal, SI, Pekcan, AG. Effect of almonds consumption on anthropometric measurements and blood parameters in overweight and obese females in a weight reduction program. Proceedings of the Nutrition Society. 2020. 79. doi:10.1017/S002966512000138X | Publication Status
692 | Urpi-Sarda, M, Casas, R, Sacanella, E, Corella, D, Andres-Lacueva, C, Llorach, R, Garrabou, G, Cardellach, F, Sala-Vila, A, Ros, E, Ruiz-Canela, M, Fito, M, Salas-Salvado, J, Estruch, R. The 3-Year Effect of the Mediterranean Diet Intervention on Inflammatory Biomarkers Related to Cardiovascular Disease. Biomedicines. 2021. 9. doi:10.3390/biomedicines9080862 | Outcome
693 | Vahid F, Hoge A, Hébert JR, Bohn T. Association of diet quality indices with serum and metabolic biomarkers in participants of the ORISCAV-LUX-2 study. | Study Design
694 | Vahid, F, Goodarzi, R, Shivappa, N, Hébert, JR, Fazeli Moghadam, E. Dietary Inflammatory Index (DII®): A significant association between coronary heart disease and DII® in Armenian adults. European Journal of Preventive Cardiology. 2020. 27:2235–2237. doi:10.1177/2047487319880030 | Intervention/Exposure; Publication Status
695 | Vamvakis, A, Gkaliagkousi, E, Lazaridis, A, Grammatikopoulou, MG, Triantafyllou, A, Nikolaidou, B, Koletsos, N, Anyfanti, P, Tzimos, C, Zebekakis, P, Douma, S. Impact of intensive lifestyle treatment (Diet plus exercise) on endothelial and vascular function, arterial stiffness and blood pressure in stage 1 hypertension: Results of the hintreat randomized controlled trial. Nutrients. 2020. 12. doi:10.3390/nu12051326 | Intervention/Exposure; Health Status
696 | van Keulen, HM, van Breukelen, G, de Vries, H, Brug, J, Mesters, I. A randomized controlled trial comparing community lifestyle interventions to improve adherence to diet and physical activity recommendations: the VitalUM study. European Journal of Epidemiology. 2021. 36:345–360. doi:10.1007/s10654-020-00708-2 | Intervention/Exposure
697 | Vasilopoulou, D, Markey, O, Kliem, KE, Fagan, CC, Grandison, AS, Humphries, DJ, Todd, S, Jackson, KG, Givens, DI, Lovegrove, JA. Reformulation initiative for partial replacement of saturated with unsaturated fats in dairy foods attenuates the increase in LDL cholesterol and improves flow-mediated dilatation compared with conventional dairy: the randomized, controlled REplacement of SaturatEd fat in dairy on Total cholesterol (RESET) study. Am J Clin Nutr. 2020. 111:739–748. doi:10.1093/ajcn/nqz344 | Intervention/Exposure
698 | Vázquez-Manjarrez, N, Guevara-Cruz, M, Flores-López, A, Pichardo-Ontiveros, E, Tovar, AR, Torres, N. Effect of a dietary intervention with functional foods on LDL-C concentrations and lipoprotein subclasses in overweight subjects with hypercholesterolemia: Results of a controlled trial. Clinical Nutrition. 2021. 40:2527–2534. doi:10.1016/j.clnu.2021.02.048 | Study Duration
699 | Vázquez-Ruiz Z, Toledo E, Vitelli-Storelli F, Goni L, de la O V, Bes-Rastrollo M, Martínez-González MÁ. Effect of Dietary Phenolic Compounds on Incidence of Cardiovascular Disease in the SUN Project; 10 Years of Follow-Up. 11. | Intervention/Exposure
700 | Verduci, E, Vizzuso, S, Ippolito, G, Vizzari, G, Amatruda, M, Radaelli, G, Agostoni, C. Effectiveness of individual vs. group-based lifestyle intervention on anthropometric and metabolic profile of obese children. Journal of pediatric gastroenterology and nutrition. 2019. 68:1020-. doi:10.1097/MPG.0000000000002403 | Publication Status
701 | Vergara, M, Hauser, ME, Aronica, L, Rigdon, J, Fielding-Singh, P, Shih, CW, Gardner, CD. Associations of changes in blood lipid concentrations with changes in dietary cholesterol intake in the context of a healthy low-carbohydrate weight loss diet: A secondary analysis of the dietfits trial. Nutrients. 2021. 13. | Intervention/Exposure
702 | Veronese, N, Cisternino, AM, Shivappa, N, Hebert, JR, Notarnicola, M, Reddavide, R, Inguaggiato, R, Guerra, V, Logroscino, A, Rotolo, O, Chiloiro, M, Leandro, G, De Leonardis, G, Tutino, V, Misciagna, G, Fontana, L, Caruso, MG, Micol group. Dietary inflammatory index and mortality: a cohort longitudinal study in a Mediterranean area. J Hum Nutr Diet. 2020. 33:138–146. doi:10.1111/jhn.12701 | Intervention/Exposure
703 | Vinke PC, Navis G, Kromhout D, Corpeleijn E. Associations of Diet Quality and All-Cause Mortality Across Levels of Cardiometabolic Health and Disease: A 7.6-Year Prospective Analysis From the Dutch Lifelines Cohort. 44. | Outcome
704 | Virtanen, HEK, Voutilainen, S, Koskinen, TT, Mursu, J, Kokko, P, Ylilauri, MPT, Tuomainen, TP, Salonen, JT, Virtanen, JK. Dietary proteins and protein sources and risk of death: The Kuopio ischaemic heart disease risk factor study. American Journal of Clinical Nutrition. 2019. 109:1462–1471. doi:10.1093/ajcn/nqz025 | Intervention/Exposure; Outcome
705 | Vitale, M, Calabrese, I, Massimino, E, Shivappa, N, Hebert, JR, Auciello, S, Grioni, S, Krogh, V, Sartore, G, Signorini, S, Rivellese, AA, Riccardi, G, Vaccaro, O, Masulli, M. Dietary inflammatory index score, glucose control and cardiovascular risk factors profile in people with type 2 diabetes. International journal of food sciences and nutrition. 2021. 72:529. | Health Status
706 | Vizzuso, S, Amatruda, M, Banderali, G, Mameli, C, Zuccotti, G, Verduci, E. One year individual or group based lifestyle intervention in obese. Impact on metabolic profile and body composition. Obesity reviews. 2020. 21. doi:10.1111/obr.13118 | Study Design; Publication Status
707 | Voortman T, Chen Z, Girschik C, Kavousi M, Franco OH, Braun KVE. Associations between macronutrient intake and coronary heart disease (CHD): The Rotterdam Study. 40. | Intervention/Exposure
708 | Vuholm, Stine, Rantanen, JesperM, Teisen, MarieN, Stark, KenD, Mølgaard, Christian, Christensen, JeppeH, Lauritzen, Lotte, Damsgaard, CamillaT. Effects of oily fish intake on cardiometabolic markers in healthy 8- to 9-y-old children: the FiSK Junior randomized trial. American Journal of Clinical Nutrition. 2019. 110:1296–1305. doi:10.1093/ajcn/nqz233 | Intervention/Exposure
709 | Wachsmuth, NB, Aberer, F, Haupt, S, Schierbauer, JR, Zimmer, RT, Eckstein, ML, Zunner, B, Schmidt, W, Niedrist, T, Sourij, H, Moser, O. The Impact of a High-Carbohydrate/Low Fat vs. Low-Carbohydrate Diet on Performance and Body Composition in Physically Active Adults: A Cross-Over Controlled Trial. Nutrients. 2022. 14. | Intervention/Exposure; Study Duration
710 | Wade, A, Davis, C, Dyer, K, Hodgson, J, Woodman, R, Keage, H, Murphy, K. Can we modify the Mediterranean diet for non-Mediterranean populations Results from two randomised controlled trials. Proceedings of the Nutrition Society. 2020. 79. doi:10.1017/S0029665120002347 | Study Duration; Publication Status
711 | Wagner, S, Lioret, S, Girerd, N, Duarte, K, Lamiral, Z, Bozec, E, Van den Berghe, L, Hoge, A, Donneau, A-F, Boivin, J-M, Merckle, L, Zannad, F, Laville, M, Rossignol, P, Nazare, J-A. Association of dietary patterns derived using reduced-rank regression with subclinical cardiovascular damage according to generation and sex in the stanislas cohort. Journal of the American Heart Association. 2020. 9. | Study Design; Outcome
712 | Wakasugi, M, Narita, I, Iseki, K, Asahi, K, Yamagata, K, Fujimoto, S, Moriyama, T, Konta, T, Tsuruya, K, Kasahara, M, Shibagaki, Y, Kondo, M, Watanabe, T. Healthy Lifestyle and Incident Hypertension and Diabetes in Participants with and without Chronic Kidney Disease: The Japan Specific Health Checkups (J-SHC) Study. Internal Medicine. 2022. 61:2841. | Intervention/Exposure
713 | Walker, ME, O’Donnell, AA, Himali, JJ, Rajendran, I, Melo Van Lent, D, Ataklte, F, Jacques, PF, Beiser, AS, Seshadri, S, Vasan, RS, Xanthakis, V. Associations of the Mediterranean-DASH Intervention for Neurodegenerative Delay Diet with cardiac remodeling in the community: The Framingham Heart Study. British Journal of Nutrition. 2021. doi:10.1017/S0007114521000660 | Study Design; Outcome
714 | Walker, ME, Xanthakis, V, Peterson, LR, Duncan, MS, Lee, J, Ma, J, Bigornia, S, Moore, LL, Quatromoni, PA, Vasan, RS, Jacques, PF. Dietary Patterns, Ceramide Ratios, and Risk of All-Cause and Cause-Specific Mortality: The Framingham Offspring Study. J Nutr. 2020. 150:2994–3004. doi:10.1093/jn/nxaa269 | Intervention/Exposure
715 | Walrabenstein, W, Wagenaar, CA, van der Leeden, M, Turkstra, F, Twisk, JWR, Boers, M, van Middendorp, H, Weijs, PJM, van Schaardenburg, D. A multidisciplinary lifestyle program for rheumatoid arthritis: the “Plants for Joints” randomized controlled trial. Rheumatology (Oxford, England). 2023. | Intervention/Exposure; Outcome; Comparator
716 | Wan Y, Tabung FK, Lee DH, Fung TT, Willett WC, Giovannucci EL. Dietary Insulinemic Potential and Risk of Total and Cause-Specific Mortality in the Nurses’ Health Study and the Health Professionals Follow-up Study. | Publication Status
717 | Wan, Y, Wang, F, Yuan, J, Li, J, Jiang, D, Zhang, J, Li, H, Wang, R, Tang, J, Huang, T, etal, . Effects of dietary fat on gut microbiota and faecal metabolites, and their relationship with cardiometabolic risk factors: a 6-month randomised controlled-feeding trial. Gut. 2019. 68:1417–1429. doi:10.1136/gutjnl-2018-317609 | Intervention/Exposure
718 | Wand H, Vujovich-Dunn C, Moodley J, Reddy T, Naidoo S. Developing and Validating Risk Algorithm for Hypertension in South Africa: Results from a Nationally Representative Cohort (2008–2017). | Study Design; Intervention/Exposure
719 | Wang DD, Li Y, Nguyen XT, Song RJ, Ho YL, Hu FB, Willett WC, Wilson PWF, Cho K, Gaziano JM, Djoussé L, On Behalf Of The Va Million Veteran Program. Dietary Sodium and Potassium Intake and Risk of Non-Fatal Cardiovascular Diseases: The Million Veteran Program. 14. | Intervention/Exposure
720 | Wang J, Lv S, Zhou Y, Sun Y, Zhu H, Yan G, Wu Y, Ma Y. The association between low carbohydrate diet scores and cardiometabolic risk factors in Chinese adults. | Study Design; Intervention/Exposure
721 | Wang K, Wang L, Liu L, Zhou P, Mo S, Luo S, Zhang Y, Wang K, Yuan Y, Yin Z, Zhang Y. Longitudinal association of egg intake frequency with cardiovascular disease in Chinese adults. | Intervention/Exposure
722 | Wang L, Li Y, Liu Y, Zhang H, Qiao T, Chu L, Luo T, Zhang Z, Dai J. Association between Different Types of Plant-Based Diets and Dyslipidemia in Middle-Aged and Elderly Chinese Participants. 15. | Study Design
723 | Wang L, Yi Z. Association of the Composite dietary antioxidant index with all-cause and cardiovascular mortality: A prospective cohort study. 9. | Intervention/Exposure
724 | Wang M, Zhou T, Song Q, Ma H, Hu Y, Heianza Y, Qi L. Ambient air pollution, healthy diet and vegetable intakes, and mortality: a prospective UK Biobank study. | Outcome
725 | Wang Y, Chen B, Zhang J, Li H, Zeng X, Zhang Z, Zhu Y, Li X, Hu A, Zhao Q, Yang W. Diets with Higher Insulinemic Potential Are Associated with Increased Risk of Overall and Cardiovascular Disease-specific Mortality. | Intervention/Exposure
726 | Wang Y, Fang Y, Witting PK, Charchar FJ, Sobey CG, Drummond GR, Golledge J. Dietary fatty acids and mortality risk from heart disease in US adults: an analysis based on NHANES. 13. | Intervention/Exposure
727 | Wang Y, Feng L, Zeng G, Zhu H, Sun J, Gao P, Yuan J, Lan X, Li S, Zhao Y, Chen X, Dong H, Chen S, Li Z, Zhu Y, Li M, Li X, Yang Z, Li H, Fang H, Xie G, Lin PH, Chen J, Wu Y. Effects of Cuisine-Based Chinese Heart-Healthy Diet in Lowering Blood Pressure Among Adults in China: Multicenter, Single-Blind, Randomized, Parallel Controlled Feeding Trial. | Study Duration
728 | Wang Z, Groen H, Cantineau AEP, van Elten TM, Karsten MDA, van Oers AM, Mol BWJ, Roseboom TJ, Hoek A. Effectiveness of a 6-Month Lifestyle Intervention on Diet, Physical Activity, Quality of Life, and Markers of Cardiometabolic Health in Women with PCOS and Obesity and Non-PCOS Obese Controls: One Size Fits All?. 13. | Intervention/Exposure
729 | Wang, DD, Nguyen, LH, Li, Y, Yan, Y, Ma, W, Rinott, E, Ivey, KL, Shai, I, Willett, WC, Hu, FB, Rimm, EB, Stampfer, MJ, Chan, AT, Huttenhower, C. The gut microbiome modulates the protective association between a Mediterranean diet and cardiometabolic disease risk. Nature Medicine. 2021. 27:333. | Outcome; Comparator
730 | Wang, F, Baden, MY, Guasch-Ferré, M, Wittenbecher, C, Li, J, Li, Y, Wan, Y, Bhupathiraju, SN, Tobias, DK, Clish, CB, Mucci, LA, Eliassen, AH, Costenbader, KH, Karlson, EW, Ascherio, A, Rimm, EB, Manson, JAE, Liang, L, Hu, FB. Plasma metabolite profiles related to plant-based diets and the risk of type 2 diabetes. Diabetologia. 2022. 65:1119. | Outcome
731 | Wang, J, Masters, WA, Bai, Y, Mozaffarian, D, Naumova, EN, Singh, GM. The International DietHealth Index: a novel tool to evaluate diet quality for cardiometabolic health across countries. BMJ Glob Health. 2020. 5. doi:10.1136/bmjgh-2019-002120 | Study Design
732 | Wang, K, Li, Y, Liu, G, Rimm, E, Chan, AT, Giovannucci, EL, Song, M. Healthy Lifestyle for Prevention of Premature Death Among Users and Nonusers of Common Preventive Medications: A Prospective Study in 2 US Cohorts. J Am Heart Assoc. 2020. 9:e016692. doi:10.1161/JAHA.119.016692 | Outcome; Comparator
733 | Wang, Mengying, Ma, Hao, Song, Qiying, Zhou, Tao, Hu, Yonghua, Heianza, Yoriko, Manson, JoAnnE, Qi, Lu. Red meat consumption and all-cause and cardiovascular mortality: results from the UK Biobank study. European Journal of Nutrition. 2022. 61:2543–2553. doi:10.1007/s00394-022-02807-0 | Intervention/Exposure
734 | Wang, Y, Tu, R, Yuan, H, Shen, L, Hou, J, Liu, X, Niu, M, Zhai, Z, Pan, M, Wang, C. Associations of unhealthy lifestyles with metabolic syndrome in Chinese rural aged females. Sci Rep. 2020. 10:2718. doi:10.1038/s41598-020-59607-x | Intervention/Exposure; Outcome
735 | Wang, Y-Y, Dai, Y, Tian, T, Zhang, J-X, Xie, W, Pan, D, Xu, D-F, Lu, Y-F, Wang, S-K, Xia, H, Sun, G-J. The effects of dietary pattern on metabolic syndrome in jiangsu province of china: Based on a nutrition and diet investigation project in Jiangsu province. Nutrients. 2021. 13. | Study Design; Country
736 | Wang, Z, Huang, Q, Wang, L, Jiang, H, Wang, Y, Wang, H, Zhang, J, Zhai, F, Zhang, B. Moderate intake of lean red meat was associated with lower risk of elevated blood pressure in chinese women: Results from the china health and nutrition survey, 1991–2015. Nutrients. 2020. 12. doi:10.3390/nu12051369 | Intervention/Exposure; Country
737 | Ward, SJ, Hill, AM, Buckley, JD, Banks, S, Dhillon, VS, Holman, SL, Morrison, JL, Coates, AM. Minimal changes in telomere length after a 12-week dietary intervention with almonds in mid-age to older, overweight and obese Australians: Results of a randomised clinical trial. British Journal of Nutrition. 2022. 127:872. | Intervention/Exposure; Outcome
738 | Wasserfurth, Paulina, Nebl, Josefine, Schuchardt, Jan Philipp, Müller, Mattea, Boßlau, Tim Konstantin, Krüger, Karsten, Hahn, Andreas. Effects of Exercise Combined with a Healthy Diet or Calanus finmarchicus Oil Supplementation on Body Composition and Metabolic Markers—A Pilot Study. Nutrients. 2020. 12:2139. doi:10.3390/nu12072139 | Intervention/Exposure; Comparator
739 | Wei, L, Fan, J, Dong, R, Zhang, M, Jiang, Y, Zhao, Q, Zhao, G, Chen, B, Li, J, Liu, S. The Effect of Dietary Pattern on Metabolic Syndrome in a Suburban Population in Shanghai, China. Nutrients. 2023. 15. | Study Design
740 | Wei, W, Jiang, W, Huang, J, Xu, J, Wang, X, Jiang, X, Wang, Y, Li, G, Sun, C, Li, Y, Han, T. Association of Meal and Snack Patterns With Mortality of All-Cause, Cardiovascular Disease, and Cancer: The US National Health and Nutrition Examination Survey, 2003 to 2014. J Am Heart Assoc. 2021. 10:e020254. doi:10.1161/JAHA.120.020254 | Intervention/Exposure
741 | Werba, JP, Giroli, MG, Simonelli, N, Vigo, L, Gorini, A, Bonomi, A, Veglia, F, Tremoli, E. Uptake and effectiveness of a primary cardiovascular prevention program in an underserved multiethnic urban community. Nutrition, Metabolism and Cardiovascular Diseases. 2022. | Study Design; Intervention/Exposure
742 | Wernicke, C, Apostolopoulou, K, Hornemann, S, Efthymiou, A, Machann, J, Schmidt, S, Primessnig, U, Bergmann, MM, Grune, T, Gerbracht, C, Herber, K, Pohrt, A, Pfeiffer, AFH, Spranger, J, Mai, K. Long-term effects of a food pattern on cardiovascular risk factors and age-related changes of muscular and cognitive function. Medicine (Baltimore). 2020. 99:e22381. doi:10.1097/MD.0000000000022381 | Intervention/Exposure
743 | Williamson, EJ, Polak, J, Simpson, JA, Giles, GG, English, DR, Hodge, A, Gurrin, L, Forbes, AB. Sustained adherence to a Mediterranean diet and physical activity on all-cause mortality in the Melbourne Collaborative Cohort Study: application of the g-formula. BMC Public Health. 2019. 19:1733. doi:10.1186/s12889-019-7919-2 | Outcome
744 | Wilson, Daniel, Driller, Matthew, Winwood, Paul, Clissold, Tracey, Johnston, Ben, Gill, Nicholas. The Effectiveness of a Combined Healthy Eating, Physical Activity, and Sleep Hygiene Lifestyle Intervention on Health and Fitness of Overweight Airline Pilots: A Controlled Trial. Nutrients. 2022. 14:1988–1988. doi:10.3390/nu14091988 | Intervention/Exposure; Comparator
745 | Wilson, DP, Williams, L, Kavey, R-EW. Hypertriglyceridemia in Youth. Journal of Pediatrics. 2022. 243:200. | Study Design
746 | Wilson, JE, Blizzard, L, Gall, SL, Magnussen, CG, Oddy, WH, Dwyer, T, Venn, AJ, Smith, KJ. An age- and sex-specific dietary guidelines index is a valid measure of diet quality in an Australian cohort during youth and adulthood. Nutrition Research. 2019. 65:43–53. doi:10.1016/j.nutres.2019.01.007 | Study Design
747 | Wing, RR, Espeland, MA, Tate, DF, Perdue, LH, Bahnson, J, Polzien, K, Ferguson Robichaud, E, LaRose, JG, Gorin, AA, Lewis, CE, etal, . Changes in Cardiovascular Risk Factors Over 6 Years in Young Adults in a Randomized Trial of Weight Gain Prevention. Obesity (Silver Spring, Md.). 2020. 28:2323–2330. doi:10.1002/oby.23003 | Intervention/Exposure
748 | Winpenny, EM, van Sluijs, EMF, Forouhi, NG. How do short-term associations between diet quality and metabolic risk vary with age?. Eur J Nutr. 2021. 60:517–527. doi:10.1007/s00394-020-02266-5 | Study Design
749 | Wittenbecher, C, Guasch-Ferré, M, Haslam, DE, Dennis, C, Li, J, Bhupathiraju, SN, Lee, C-H, Qi, Q, Liang, L, Eliassen, AH, Clish, C, Sun, Q, Hu, FB. Changes in metabolomics profiles over ten years and subsequent risk of developing type 2 diabetes: Results from the Nurses’ Health Study. eBioMedicine. 2022. 75. | Outcome
750 | Wozniak, H, Larpin, C, de Mestral, C, Guessous, I, Reny, JL, Stringhini, S. Vegetarian, pescatarian and flexitarian diets: sociodemographic determinants and association with cardiovascular risk factors in a Swiss urban population. Br J Nutr. 2020. 124:844–852. doi:10.1017/S0007114520001762 | Study Design
751 | Wright KD, Klatt MD, Adams IR, Nguyen CM, Mion LC, Tan A, Monroe TB, Rose KM, Scharre DW. Mindfulness in Motion and Dietary Approaches to Stop Hypertension (DASH) in Hypertensive African Americans. 69. | Intervention/Exposure; Study Duration
752 | Wu S, Zhang X, Zhao X, Hao X, Zhang S, Li P, Tan J. Preconception Dietary Patterns and Associations With IVF Outcomes: An Ongoing Prospective Cohort Study. 9. | Health Status; Outcome
753 | Wu X, Tang W, Tang D, Hu Y, Zhang N, Dai S, Pan Y, Li J, Guan H, Meng J, Zhao X, Xiao X, Yin J. Two a posteriori dietary patterns are associated with risks of hyperuricemia among adults in less-developed multiethnic regions in Southwest China. 110. | Outcome
754 | Wu, Y, Juraschek, SP, Hu, JR, Miller, ER. Higher carbohydrate amount and lower glycemic index increase hunger, diet satisfaction, and gastrointestinal symptom of heartburn: results from the omnicarb randomized clinical trial. Circulation. 2019. 140. doi:10.1161/circ.140.suppl_1.10951 | Study Duration; Publication Status
755 | Wurtz, AML, Hansen, MD, Tjonneland, A, Rimm, EB, Schmidt, EB, Overvad, K, Jakobsen, MU. Replacement of potatoes with other vegetables and risk of myocardial infarction in the Danish Diet, Cancer and Health cohort. Br J Nutr. 2021. 1–8. doi:10.1017/S0007114521000349 | Intervention/Exposure
756 | Xia X, Toh DWK, Ng SL, Zharkova O, Poh KK, Foo RSY, Wang JW, Kim JE. Impact of following a healthy dietary pattern with co-consuming wolfberry on number and function of blood outgrowth endothelial cells from middle-aged and older adults. | Intervention/Exposure; Comparator
757 | Xia, Y, Cao, L, Zhang, Q, Liu, L, Zhang, S, Meng, G, Wu, H, Gu, Y, Sun, S, Wang, X, Zhou, M, Jia, Q, Song, K, Wu, Q, Niu, K, Zhao, Y. Adherence to a vegetable dietary pattern attenuates the risk of non-alcoholic fatty liver disease in incident type 2 diabetes: The TCLSIH cohort study. Journal of Internal Medicine. 2022. 291:469. | Outcome
758 | Xiao X, Qin Z, Lv X, Dai Y, Ciren Z, Yangla Y, Zeng P, Ma Y, Li X, Wang L, Hu Y, Yang F, Fan C, Tang D, Dai S, Zhang N, Xie X, Yin J, Zhao X. Dietary patterns and cardiometabolic risks in diverse less-developed ethnic minority regions: results from the China Multi-Ethnic Cohort (CMEC) Study. 15. | Study Design
759 | Xu C, Cao Z, Yang H, Hou Y, Wang X, Wang Y. Association Between the EAT-Lancet Diet Pattern and Risk of Type 2 Diabetes: A Prospective Cohort Study. 8. | Outcome
760 | Xu C, Cao Z. Cardiometabolic diseases, total mortality, and benefits of adherence to a healthy lifestyle: a 13-year prospective UK Biobank study. 20. | Intervention/Exposure
761 | Xu, X, Shi, Z, Liu, G, Chang, D, Inglis, SC, Hall, JJ, Schutte, AE, Byles, JE, Parker, D. The Joint Effects of Diet and Dietary Supplements in Relation to Obesity and Cardiovascular Disease over a 10-Year Follow-Up: A Longitudinal Study of 69,990 Participants in Australia. Nutrients. 2021. 13. doi:10.3390/nu13030944 | Comparator
762 | Yamada, S, Inoue, G, Ooyane, H, Nishikawa, H. Changes in body weight, dysglycemia, and dyslipidemia after moderately low-carbohydrate diet education (Locabo challenge program) among workers in japan. Diabetes, Metabolic Syndrome and Obesity: Targets and Therapy. 2021. 14:2863–2870. doi:10.2147/DMSO.S317371 | Study Design; Intervention/Exposure
763 | Yang J, Yang A, Yeung S, Woo J, Lo K. Joint Associations of Food Groups with All-Cause and Cause-Specific Mortality in the Mr. OS and Ms. OS Study: A Prospective Cohort. 14. | Intervention/Exposure
764 | Yang Y, Yu D, Piao W, Huang K, Zhao L. Nutrient-Derived Beneficial for Blood Pressure Dietary Pattern Associated with Hypertension Prevention and Control: Based on China Nutrition and Health Surveillance 2015–2017. 14. | Study Design
765 | Yang, Q, Cogswell, ME, Dana Flanders, W, Hong, Y, Zhang, Z, Loustalot, F, Gillespie, C, Merritt, R, Hu, FB. Trends in cardiovascular health metrics and associations with all-cause and CVD mortality among us adults. JAMA. 2012. 307:1273. | Study Design; Publication Date
766 | Yau, K-Y, Law, P-S, Wong, C-N. Cardiac and Mental Benefits of Mediterranean-DASH Intervention for Neurodegenerative Delay (MIND) Diet plus Forest Bathing (FB) versus MIND Diet among Older Chinese Adults: A Randomized Controlled Pilot Study. International Journal of Environmental Research and Public Health. 2022. 19. | Study Duration
767 | Yazdanpanah, Z, Salehi-Abargouei, A, Mollahosseini, M, Sheikhha, MH, Mirzaei, M, Mozaffari-Khosravi, H. The cluster of differentiation 36 (CD36) rs1761667 polymorphism interacts with dietary patterns to affect cardiometabolic risk factors and metabolic syndrome risk in apparently healthy individuals. British Journal of Nutrition. 2023. | Study Design
768 | Yi K, Cui S, Tang M, Wu Y, Xiang Y, Yu Y, Tong X, Jiang Y, Zhao Q, Zhao G. Adherence to DASH Dietary Pattern and Its Association with Incident Hyperuricemia Risk: A Prospective Study in Chinese Community Residents. 14. | Outcome
769 | Yi SY, Steffen LM, Haring B, Rebholz CM, Mosley TH, Shah AM. Associations of the Dietary Approaches to Stop Hypertension dietary pattern with cardiac structure and function. | Outcome
770 | Yisahak, SF, Mumford, SL, Grewal, J, Li, M, Zhang, C, Grantz, KL, Hinkle, SN. Maternal diet patterns during early pregnancy in relation to neonatal outcomes. American Journal of Clinical Nutrition. 2021. 114:358. | Outcome
771 | Yisahak, SF, Hinkle, SN, Mumford, SL, Li, M, Andriessen, VC, Grantz, KL, Zhang, C, Grewal, J. Vegetarian diets during pregnancy, and maternal and neonatal outcomes. Int J Epidemiol. 2021. 50:165–178. doi:10.1093/ije/dyaa200 | Intervention/Exposure
772 | Yokose, C, McCormick, N, Rai, SK, Lu, N, Curhan, G, Schwarzfuchs, D, Shai, I, Choi, HK. Effects of Low-Fat, Mediterranean, or Low-Carbohydrate Weight Loss Diets on Serum Urate and Cardiometabolic Risk Factors: A Secondary Analysis of the Dietary Intervention Randomized Controlled Trial (DIRECT). Diabetes Care. 2020. 43:2812–2820. doi:10.2337/dc20-1002 | Intervention/Exposure
773 | Yoshida H. Is the Japan Diet Instrumental in Preventing Cardiovascular Diseases?. 28. | Study Design
774 | Yu, G, Fu, H, Huang, W, Zhang, N, Deng, D, Li, G, Lei, H. A Dietary Pattern of Higher Fish, Egg, Milk, Nut, Vegetable and Fruit, and Lower Salt Intake Correlates With the Prevalence and Control of Hypertension. American Journal of Hypertension. 2018. 31:679. | Study Design; Country
775 | Yu, S, Guo, X, Li, G, Yang, H, Sun, G, Zheng, L, Sun, Y. Gender discrepancy of incidence and risk factors of metabolic syndrome among rural Chinese from 2012–2013 to 2015–2017. Diabetol Metab Syndr. 2020. 12:48. doi:10.1186/s13098-020-00542-2 | Outcome
776 | Yuan, WL, Bernard, JY, Armand, M, Sarté, C, Charles, MA, Heude, B. Associations of Maternal Consumption of Dairy Products during Pregnancy with Perinatal Fatty Acids Profile in the EDEN Cohort Study. Nutrients. 2022. 14. | Intervention/Exposure
777 | Zafarmand, MH, Spanjer, M, Nicolaou, M, Wijnhoven, HAH, van Schaik, BDC, Uitterlinden, AG, Snieder, H, Vrijkotte, TGM. Influence of Dietary Approaches to Stop Hypertension-Type Diet, Known Genetic Variants and Their Interplay on Blood Pressure in Early Childhood: ABCD Study. Hypertension. 2020. 75:59–70. doi:10.1161/HYPERTENSIONAHA.118.12292 | Study Design
778 | Zamanillo-Campos, R, Chaplin, A, Romaguera, D, Abete, I, Salas-Salvadó, J, Martín, V, Estruch, R, Vidal, J, Ruiz-Canela, M, Babio, N, Fiol, F, de Paz, JA, Casas, R, Olbeyra, R, Martínez-González, MA, García-Gavilán, JF, Goday, A, Fernandez-Lazaro, CI, Martínez, JA, Hu, FB, Konieczna, J. Longitudinal association of dietary carbohydrate quality with visceral fat deposition and other adiposity indicators. Clinical Nutrition. 2022. 41:2264. | Intervention/Exposure
779 | Zamora-Ros, R, Cayssials, V, Cleries, R, Redondo, ML, Sánchez, MJ, Rodríguez-Barranco, M, Sánchez-Cruz, JJ, Mokoroa, O, Gil, L, Amiano, P, Navarro, C, Chirlaque, MD, Huerta, JM, Barricarte, A, Ardanaz, E, Moreno-Iribas, C, Agudo, A. Moderate egg consumption and all-cause and specific-cause mortality in the Spanish European Prospective into Cancer and Nutrition (EPIC-Spain) study. European Journal of Nutrition. 2019. 58:2003–2010. doi:10.1007/s00394-018-1754-6 | Intervention/Exposure
780 | Zeng, Xufen, Li, Xiude, Zhang, Zhuang, Li, Hairong, Wang, Yingying, Zhu, Yu, Hu, Anla, Zhao, Qihong, Tang, Min, Zhang, Xuehong, Huang, Jiaqi, Yang, Wanshui. A prospective study of carbohydrate intake and risk of all-cause and specific-cause mortality. European Journal of Nutrition. 2022. 61:3149–3160. doi:10.1007/s00394-022-02877-0 | Intervention/Exposure
781 | Zhang N, Xiao X, Xu J, Zeng Q, Li J, Xie Y, Guo B, Dai S, Zhu X, Lei Y, Duojizhuoma, Yin J, Zhao X. Dietary Approaches to Stop Hypertension (DASH) diet, Mediterranean diet and blood lipid profiles in less-developed ethnic minority regions. | Study Design
782 | Zhang N, Zhou M, Li M, Ma G. Effects of Smartphone-Based Remote Interventions on Dietary Intake, Physical Activity, Weight Control, and Related Health Benefits Among the Older Population With Overweight and Obesity in China: Randomized Controlled Trial. 25. | Intervention/Exposure; Comparator
783 | Zhang X, Lu J, Yang Y, Cui J, Zhang X, Xu W, Song L, Wu C, Wang Q, Wang Y, Wang R, Li X. Cardiovascular disease prevention and mortality across 1 million urban populations in China: data from a nationwide population-based study. 7. | Intervention/Exposure
784 | Zhang, H, Zeng, Y, Yang, H, Hu, Y, Hu, Y, Chen, W, Ying, Z, Sun, Y, Qu, Y, Li, Q, Valdimarsdottir, UA, Song, H. Familial factors, diet, and risk of cardiovascular disease: a cohort analysis of the UK Biobank. Am J Clin Nutr. 2021. doi:10.1093/ajcn/nqab261 | Intervention/Exposure
785 | Zhang, S, Zhuang, X, Lin, X, Zhong, X, Zhou, H, Sun, X, Xiong, Z, Huang, Y, Fan, Y, Guo, Y, Du, Z, Liao, X. Low-Carbohydrate Diets and Risk of Incident Atrial Fibrillation: A Prospective Cohort Study. Journal of the American Heart Association. 2019. 8. doi:10.1161/JAHA.119.011955 | Intervention/Exposure
786 | Zhang, Y-Bo, Chen, C, Pan, X-Fi, Guo, J, Li, Y, Franco, OH, Liu, G, Pan, A. Associations of healthy lifestyle and socioeconomic status with mortality and incident cardiovascular disease: Two prospective cohort studies. The BMJ. 2021. 373. | Intervention/Exposure; Outcome
787 | Zhang, Y-J, Li, Z-H, Shen, D, Zhang, P-D, Fu, S-H, Yao, Y, Wang, J-X, Chen, P-L, Zhang, P, Zhang, X-R, Mao, C. Association of Combined Lifestyle and Polygenetic Risk with Incidence of Venous Thromboembolism: A Large Population-Based Cohort Study. Thrombosis and Haemostasis. 2022. 122:1549. | Health Status; Outcome
788 | Zhao J, Guo W, Wang J, Wang T. Exploring the Association of Dietary Patterns with the Risk of Hypertension Using Principal Balances Analysis and Principal Component Analysis. | Country
789 | Zhao R, Zhao L, Gao X, Yang F, Yang Y, Fang H, Ju L, Xu X, Guo Q, Li S, Cheng X, Cai S, Yu D, Ding G. Geographic Variations in Dietary Patterns and Their Associations with Overweight/Obesity and Hypertension in China: Findings from China Nutrition and Health Surveillance (2015–2017). 14. | Study Design
790 | Zhao, H, Andreyeva, T. Diet Quality and Health in Older Americans. Nutrients. 2022. 14. | Study Design
791 | Zhao, Y, Naumova, EN, Bobb, JF, Claus Henn, B, Singh, GM. Joint Associations of Multiple Dietary Components with Cardiovascular Disease Risk: A Machine-Learning Approach. American Journal of Epidemiology. 2021. 190:1353. | Intervention/Exposure; Outcome
792 | Zhen J, Liu S, Zhao G, Peng H, Xu A, Li C, Wu J, Cheung BMY. Impact of healthy lifestyles on risk of hypertension in the Chinese population: finding from SHUN-CVD study. | Study Design; Intervention/Exposure
793 | Zheng, C, Pettinger, M, Gowda, GAN, Lampe, JW, Raftery, D, Tinker, LF, Huang, Y, Navarro, SL, O’Brien, DM, Snetselaar, L, Liu, S, Wallace, RB, Neuhouser, ML, Prentice, RL. Biomarker-calibrated Red and Combined Red and Processed Meat Intakes with Chronic Disease Risk in a Cohort of Postmenopausal Women. The Journal of nutrition. 2022. | Intervention/Exposure
794 | Zhong, VW, Allen, NB, Greenland, P, Carnethon, MR, Ning, H, Wilkins, JT, Lloyd-Jones, DM, Van Horn, L. Protein foods from animal sources, incident cardiovascular disease and all-cause mortality: a substitution analysis. Int J Epidemiol. 2021. 50:223–233. doi:10.1093/ije/dyaa205 | Intervention/Exposure
795 | Zhou J, Leepromrath S, Zhou D. Dietary diversity indices versus dietary guideline-based indices and their associations with non-communicable diseases, overweight and energy intake: evidence from China. | Study Design; Country
796 | Zhou, L, Feng, Y, Yang, Y, Zhao, X, Fan, Y, Rong, J, Liu, D, Zhao, L, Yu, Y. Diet behaviours and hypertension inUS adults: The NationalHealth and Nutrition Examination Survey 2013–2014. Journal of Hypertension. 2019. 37:1230–1238. doi:10.1097/HJH.0000000000002037 | Study Design
797 | Zhou, YF, Song, XY, Wu, J, Chen, GC, Neelakantan, N, van Dam, RM, Feng, L, Yuan, JM, Pan, A, Koh, WP. Association Between Dietary Patterns in Midlife and Healthy Ageing in Chinese Adults: The Singapore Chinese Health Study. J Am Med Dir Assoc. 2021. 22:1279–1286. doi:10.1016/j.jamda.2020.09.045 | Outcome
798 | Zhu, R, Fogelholm, M, Jalo, E, Poppitt, SD, Silvestre, MP, Møller, G, Huttunen-Lenz, M, Stratton, G, Sundvall, J, Macdonald, IA, Handjieva-Darlenska, T, Handjiev, S, Navas-Carretero, S, Martinez, JA, Muirhead, R, Brand-Miller, J, Raben, A. Animal-based food choice and associations with long-term weight maintenance and metabolic health after a large and rapid weight loss: The PREVIEW study. Clinical Nutrition. 2022. 41:817. | Intervention/Exposure
799 | Zhu, X-C, Lin, J, Wang, Q, Liu, H, Qiu, L, Fang, D-Z. Associations of lipoprotein lipase gene rs326 with changes of lipid profiles after a high-carbohydrate and low-fat diet in healthy Chinese Han youth. International Journal of Environmental Research and Public Health. 2014. 11:4544. | Study Duration
800 | Zinn, C, McPhee, J, Harris, N, Williden, M, Prendergast, K, Schofield, G. A 12-week low-carbohydrate, high-fat diet improves metabolic health outcomes over a control diet in a randomised controlled trial with overweight defence force personnel. Applied physiology, nutrition & metabolism. 2017. 42:1158–1164. doi:10.1139/apnm-2017-0260 | Intervention/Exposure
801 | Zomeño, MD, Lassale, C, Perez-Vega, A, Perez-Fernández, S, Basora, J, Babió, N, Llimona, R, Paz-Graniel, I, Muñoz, J, Salas, J, Pintó, X, Sacanella, E, Fitó, M, Subirana, I, Schröder, H, Goday, A, Castaner, O. Halo effect of a Mediterranean-lifestyle weight-loss intervention on untreated family members’ weight and physical activity: a prospective study. International Journal of Obesity. 2021. 45:1240–1248. doi:10.1038/s41366-021-00763-z | Outcome
802 | Zuercher MD, Harvey DJ, Santiago-Torres M, Au LE, Shivappa N, Shadyab AH, Allison M, Snetselaar L, Liu B, Robbins JA, Hébert JR, Garcia L. Dietary inflammatory index and cardiovascular disease risk in Hispanic women from the Women’s Health Initiative. 22. | Intervention/Exposure