# Appendix 4 Literature search strategy

## Search from the existing review

The literature search conducted for the existing review identified articles published between January 1980- January 2017. For the complete search documentation, refer to:

Suggested citation: Raghavan R, Dreibelbis C, Kingshipp BJ, Wong, YP, Terry N, Abrams B, Bartholomew A, Bodnar LM, Gernand A, Rasmussen K, Siega-Riz AM, Stang JS, Casavale KO, Spahn JM, Stoody E. Dietary Patterns before and during Pregnancy and Risk of Hypertensive Disorders of Pregnancy: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0101.

## Search A

This search was conducted to update the search from the existing review (referenced above) and identify articles published between the included dates of that existing review and Search B (detailed below). This search was used in both this review and in the systematic review that examines the relationship between dietary patterns consumed during pregnancy and risk of gestational diabetes mellitus.

[underlined: Database: PubMed]

Provider: U.S. National Library of Medicine

Date(s) Searched: February 23, 2022

Dates Covered: January 1, 2017- October 21, 2019

Table A 4 Search for PubMed (Search A)

Search # | Concept | String
#1 | Dietary Patterns | (“dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “diet variety”[tiab] OR “dietary variety”[tiab] OR “varied diet”[tiab] OR “dietary guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary intake*”[tiab] OR “eating style*”[tiab] OR “Diet, Mediterranean”[Mesh] OR “Mediterranean Diet*”[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR “Dietary Approaches To Stop Hypertension Diet*”[tiab] OR “DASH diet*”[tiab] OR “Diet, Gluten-Free”[Mesh] OR “Gluten Free diet*”[tiab] OR “prudent diet*”[tiab] OR “Diet, Paleolithic”[Mesh] OR “Paleolithic Diet*”[tiab] OR “Diet, Vegetarian”[Mesh] OR “vegetarian diet*”[tiab] OR “vegan diet*”[tiab] OR “Diet, Healthy”[Mesh] OR “healthy diet*”[tiab] OR “plant based diet*”[tiab] OR “Diet, Western”[Mesh] OR “western diet*”[tiab] OR “Nordic Diet*”[tiab] OR “Okinawan diet*”[tiab] OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “high-fat diet*”[tiab] OR “low fat diet*”[tiab] OR “Diet, Sodium-Restricted”[Mesh] OR “low-sodium diet*”[tiab] OR “low salt diet*”[tiab] OR ((“Guideline Adherence”[Mesh] OR “guideline adherence*”[tiab])AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR “diet score*”[tiab] OR “diet quality score*”[tiab] OR “diet quality index*”[tiab] OR kidmed[tiab] OR “diet index*”[tiab] OR “dietary index*”[tiab] OR “food score*”[tiab] OR MedDietScore[tiab] OR “healthy eating index”[tiab])
#2 | Hypertension | hypertensi*[tiab] OR Hypertension[MeSH:NoExp] OR “Pre-Eclamp*”[tiab] OR preeclamp*[tiab] OR “Hypertension, Pregnancy-Induced”[MeSH] OR Eclamp*[tiab] OR “Blood Pressure”[MeSH:NoExp] OR “high blood pressure”[tiab]
#3 | Diabetes | (“Diabetes Mellitus”[Mesh:NoExp] OR “Prediabetic State”[Mesh] OR “prediabet*”[tiab] OR “pre diabet*”[tiab] OR “Insulin Resistance”[Mesh] OR “insulin resistance”[tiab] OR “insulin resistant”[tiab] OR “glucose intolerance”[tiab] OR “glucose intolerant”[tiab] OR “glucose tolerance”[tiab] OR “glucose tolerant”[tiab] OR “Glycated Hemoglobin A”[Mesh] OR “hemoglobin A1c”[tiab] OR hba1c[tiab] OR “hba 1c”[tiab] OR “haemoglobin A1c”[tiab] OR “Hyperglycemia”[Mesh] OR “hyperglycemia”[tiab] OR hyperglycaemia[tiab] OR “Hypoglycemia”[Mesh] OR “hypoglycemia”[tiab] OR hypoglycaemia[tiab] OR ((impaired[tiab] OR glucose[tiab]) AND fasting[tiab]) OR “blood glucose”[MeSH] OR “blood glucose”[tiab] OR “plasma glucose”[tiab] OR “serum glucose”[tiab] OR “glycemi*”[tiab] OR glycaemi*[tiab] OR “blood sugar”[tiab] OR dysglycemi*[tiab] OR dysglycaemi*[tiab] OR hyperinsulinism[MeSH] OR hyperinsulin*[tiab] OR “Diabetes, Gestational”[Mesh] OR (gestation*[tiab] AND diabet*[tiab]) OR (“Maternal Nutritional Physiological Phenomena”[Mesh] AND diabet*[tiab]))
#4 | #2 OR #3
#5 | Pregnancy | Pregnancy[Mesh] OR “Pregnancy Complications”[Mesh] OR “Maternal Exposure”[Mesh] OR “Pregnant Women”[Mesh] OR “Prenatal Exposure Delayed Effects”[Mesh]OR pregnan*[tiab] OR prepregnancy[tiab] OR prenatal[tiab] OR perinatal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation*[tiab] OR natal[tiab] OR antenatal[tiab]
#6 | #1 AND #4 AND #5
#7 | Limits | #6 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Language: English; Publication Date: Jan 1, 2017-Oct 21, 2019

[underlined: Database: Embase]

Provider: Elsevier

Date(s) Searched: February 23, 2022

Dates Covered: January 1, 2017-October 21, 2019

Table A 5 Search for Embase (Search A)

Search # | Concept | String
#1 | Dietary Patterns | ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/exp OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein restriction’/exp OR ‘sodium restriction’/exp OR ‘nordic diet’/de OR ‘protein diet’/exp; OR ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality’:ab,ti OR ‘dietary quality’:ab,ti OR ‘diet variety’:ab,ti OR ‘dietary variety’:ab,ti OR ‘varied diet’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘Mediterranean Diet*’:ab,ti OR ‘Dietary Approaches To Stop Hypertension Diet*’:ab,ti OR ‘DASH diet*’:ab,ti OR ‘Gluten Free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘Paleolithic Diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘healthy diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘Nordic Diet*’:ab,ti OR ‘Okinawan Diet*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti OR ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘diet quality index*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food score*’:ab,ti OR MedDietScore:ab,ti OR ‘healthy eating index’:ab,ti; OR (‘guideline adherence*’ AND (diet OR dietary OR food OR beverage* OR nutrition*)):ab,ti
#2 | Hypertension | ‘hypertension’/de OR ‘maternal hypertension’/exp OR ‘blood pressure’/de OR hypertensi*:ab,ti OR ‘pre-eclamp*’:ab,ti OR preeclamp*:ab,ti OR eclamp*:ab,ti OR ‘high blood pressure’:ab,ti
#3 | Diabetes | ‘Diabetes Mellitus’/de OR ‘diabetic obesity’/exp OR ‘impaired glucose tolerance’/exp OR ‘insulin resistance’/exp OR ‘Hypoglycemia’/exp OR ‘glucose blood level’/exp OR ‘hyperinsulinism’/exp OR ‘pregnancy diabetes mellitus’/exp; OR ‘prediabet*’:ab,ti OR ‘pre diabet*’:ab,ti OR ‘insulin resistance’:ab,ti OR ‘insulin resistant’:ab,ti OR ‘glucose intolerance’:ab,ti OR ‘glucose intolerant’:ab,ti OR ‘glucose tolerance’:ab,ti OR ‘glucose tolerant’:ab,ti OR ‘hemoglobin A1c’:ab,ti OR ‘hba1c’:ab,ti OR ‘hba 1c’:ab,ti OR ‘haemoglobin A1c’:ab,ti OR ‘hyperglycemia’:ab,ti OR ‘hyperglycaemia’:ab,ti OR ‘hypoglycemia’:ab,ti OR ‘hypoglycaemia’:ab,ti OR ((‘impaired’:ab,ti OR ‘glucose’:ab,ti) AND ‘fasting’:ab,ti) OR ‘blood glucose’:ab,ti OR ‘plasma glucose’:ab,ti OR ‘serum glucose’:ab,ti OR ‘glycemi*’:ab,ti OR glycaemi*:ab,ti OR ‘blood sugar’:ab,ti OR dysglycemi*:ab,ti OR dysglycaemi*:ab,ti OR hyperinsulin*:ab,ti OR (‘gestation*’:ab,ti AND ‘diabet*’:ab,ti)
#4 | #2 OR #3
#5 | Pregnancy | ‘Pregnancy’/exp OR ‘Pregnancy Complications’/exp OR ‘Maternal Exposure’/exp OR ‘perinatal exposure’/exp OR ‘Pregnant Woman’/exp OR ‘Perinatal Period’/exp OR ‘Prenatal exposure’/exp OR pregnan*:ab,ti OR prepregnancy:ab,ti OR prenatal:ab,ti OR perinatal:ab,ti OR ‘pre-conception’:ab,ti OR preconception:ab,ti OR ‘peri-conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri-partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR antenatal:ab,ti
#6 | #1 AND #4 AND #5
#7 | Limits | #6 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti) AND [2017-2019]/py

[underlined: Database: Cochrane Central Register of Controlled Trials (CENTRAL)]

Provider: John Wiley & Sons

Date(s) Searched: February 23, 2022

Dates Covered: January 1, 2017- October 21, 2019

Table A 6 Search for Cochrane CENTRAL (Search A)

Search # | Concept | String
#1 | Dietary Patterns | [mh “Diet, Mediterranean”] OR [mh “Dietary Approaches To Stop Hypertension”] OR [mh “Diet, Gluten-Free”] OR [mh “Diet, Paleolithic”] OR [mh “Diet, Vegetarian”] OR [mh “Diet, Healthy”] OR [mh “Diet, Western”] OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, Sodium-Restricted”] OR [mh “Guideline Adherence”]; OR (“dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “Okinawan diet” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet*” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*” OR “low fat diet*” OR “low-sodium diet*” OR “low salt diet*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index”):ti,ab,kw; OR (“guideline adherence*” AND (diet OR dietary OR food OR beverage* OR nutrition*)):ti,ab,kw
#2 | Hypertension | [mh ^“Blood Pressure”] OR [mh “Hypertension”] OR [mh “Hypertension, Pregnancy-Induced”]; OR (hypertensi* OR “Pre-Eclamp*” OR preeclamp* OR Eclamp* OR “high blood pressure”):ti,ab,kw
#3 | Diabetes | [mh ^“Diabetes Mellitus”] OR [mh “Prediabetic State”] OR [mh “Insulin Resistance”] OR [mh “Hyperglycemia”] OR [mh “Glycated Hemoglobin A”] OR [mh “Hypoglycemia”] OR [mh “blood glucose”] OR [mh hyperinsulinism] OR [mh “Diabetes, Gestational”]; OR (“prediabet*” OR “pre diabet*” OR “insulin resistance” OR “insulin resistant” OR “glucose intolerance” OR “glucose intolerant” OR “glucose tolerance” OR “glucose tolerant” OR “hemoglobin A1c” OR “hba1c” OR “hba 1c” OR “haemoglobin A1c” OR “hyperglycemia” OR hyperglycaemia OR “hypoglycemia” OR “hypoglycaemia” OR ((impaired OR glucose) AND fasting) OR “blood glucose” OR “plasma glucose” OR “serum glucose” OR “glycemi*” OR glycaemi* OR “blood sugar” OR dysglycemi* OR dysglycaemi* OR hyperinsulin* OR (gestation* AND diabet*)):ti,ab,kw
#4 | #2 OR #3
| Pregnancy | [mh Pregnancy] OR [mh “Pregnancy Complications”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Peripartum Period”] OR [mh “Prenatal Exposure Delayed Effects”] OR (pregnan* OR prepregnancy OR prenatal OR perinatal OR “pre-conception” OR preconception OR “peri-conception” OR periconception OR peripartum OR “peri-partum” OR gestation* OR natal OR antenatal):ti,ab,kw
#5 | #1 AND #4 AND #5 | In trials, word variations searched, year first published 2017-2019

[underlined: Database: CINAHL]

Provider: EBSCO

Date(s) Searched: February 23, 2022

Dates Covered: January 1, 2017-October 21, 2019

Table A 7 Search for CINAHL (Search A)

Search # | Concept | String
#1 | Dietary Patterns | (MH “Mediterranean Diet”) OR (MH “DASH Diet”) OR (MH “Diet, Gluten-Free”) OR (MH “Diet, Paleolithic”) OR (MH “Vegetarianism”) OR (MH “Diet, Western”) OR (MH “Diet, Fat-Restricted”) OR (MH “Diet, Sodium-Restricted”) OR (MH “Restricted Diet”) OR (MH “Diet, High Protein”) OR (MH “Diet, Nordic”) OR (MH “Plant-Based Diet”) OR (MH “Guideline Adherence”); OR (TI “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “Okinawan diet” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet*” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*” OR “low fat diet*” OR “low-sodium diet*” OR “low salt diet*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index”) OR (AB “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “Okinawan diet” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet*” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*” OR “low fat diet*” OR “low-sodium diet*” OR “low salt diet*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index”); OR TI (“guideline adherence*” AND (diet OR dietary OR food OR beverage* OR nutrition*) OR AB (“guideline adherence*” AND (diet OR dietary OR food OR beverage* OR nutrition*))
#2 | Hypertension | (MH “Blood Pressure”) OR (MH Hypertension) OR (TI hypertensi* OR “Pre-Eclamp*” OR preeclamp* OR Eclamp* OR “high blood pressure”) OR (AB hypertensi* OR “Pre-Eclamp*” OR preeclamp* OR Eclamp* OR “high blood pressure”)
#3 | Diabetes | (MH “Diabetes Mellitus”) OR (MH “Diabetes Mellitus, Gestational”) OR (MH “Prediabetic State”) OR (MH “Insulin Resistance+”) OR (MH “Hyperglycemia+”) OR (MH “Hemoglobin A, Glycosylated”) OR (MH “Hypoglycemia+”) OR (MH “blood glucose”) OR (MH “hyperinsulinism+”); OR (OR “prediabet*” OR “pre diabet*” OR “insulin resistance” OR “insulin resistant” OR “glucose intolerance” OR “glucose intolerant” OR “glucose tolerance” OR “glucose tolerant” OR “hemoglobin A1c” OR “hba1c” OR “hba 1c” OR “haemoglobin A1c” OR “hyperglycemia” OR hyperglycaemia OR “hypoglycemia” OR “hypoglycaemia” OR ((impaired OR glucose) AND fasting) OR “blood glucose” OR “plasma glucose” OR “serum glucose” OR “glycemi*” OR glycaemi* OR “blood sugar” OR dysglycemi* OR dysglycaemi* OR hyperinsulin* OR (gestation* AND diabet*)) OR (“prediabet*” OR “pre diabet*” OR “insulin resistance” OR “insulin resistant” OR “glucose intolerance” OR “glucose intolerant” OR “glucose tolerance” OR “glucose tolerant” OR “hemoglobin A1c” OR “hba1c” OR “hba 1c” OR “haemoglobin A1c” OR “hyperglycemia” OR hyperglycaemia OR “hypoglycemia” OR “hypoglycaemia” OR ((impaired OR glucose) AND fasting) OR “blood glucose” OR “plasma glucose” OR “serum glucose” OR “glycemi*” OR glycaemi* OR “blood sugar” OR dysglycemi* OR dysglycaemi* OR hyperinsulin* OR (gestation* AND diabet*)
#4 | #2 OR #3
#5 | Pregnancy | (MH “Pregnancy+”) OR (MH “Pregnancy Complications+”) OR (MH “Maternal Exposure”) OR (MH “Prenatal Exposure Delayed Effects”) OR (MH “Expectant Mothers”) OR (TI pregnan* OR prepregnancy OR prenatal OR perinatal OR “pre-conception” OR preconception OR “peri-conception” OR periconception OR peripartum OR “peri-partum” OR gestation* OR natal OR antenatal) OR (AB pregnan* OR prepregnancy OR prenatal OR perinatal OR “pre-conception” OR preconception OR “peri-conception” OR periconception OR peripartum OR “peri-partum” OR gestation* OR natal OR antenatal)
#6 | #1 AND #4 AND #5
#7 | Limits | #6 NOT ((MH “Animals+”) OR (MH “Animal Studies”)); NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication); English, Apply equivalent subjects; Published Date: January 2017 – October 2019

## Search B

This search encompasses a wider range of terms than Search A because it is also used in the systematic review that examines the relationship between dietary patterns and cardiovascular disease. The search was first run on October 5, 2021 and was then periodically run using NESR’s continuous evidence monitoring methods^*^ through May 2023.

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

[underlined: Database: PubMed]

Provider: U.S. National Library of Medicine

Date(s) Searched: October 5, 2021 (initial search); October 5, 2021 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: October 21, 2019 – May 31, 2023

Table A 8 Search for PubMed (Search B)

Search # | Concept | String
#1 | Cardiovascular diseases | “Cardiovascular Diseases”[Mesh:NoExp] OR “cardiovascular disease*”[tiab] OR “coronary artery disease”[tiab] OR “heart disease*”[tiab] OR “Heart Failure”[Mesh] OR “heart failure”[tiab] OR “myocardial infarction*”[tiab] OR “Myocardial Ischemia”[Mesh] OR “myocardial ischemia*”[tiab] OR “Stroke”[Mesh] OR “stroke*”[tiab] OR “angina”[tiab] OR “heart attack*”[tiab] OR “Venous Thrombosis”[Mesh] OR “venous thrombosis”[tiab] OR “hypertension”[tiab] OR Blood Pressure[Mesh:NoExp] OR “high blood pressure”[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR “HDL cholesterol”[tiab] OR “Cholesterol, LDL”[Mesh] OR “LDL cholesterol”[tiab] OR “total cholesterol”[tiab] OR “blood cholesterol”[tiab] OR “Triglycerides”[Mesh] OR “triglycerides”[tiab] OR “Hypertension”[Mesh:NoExp] OR hypertensi*[tiab] OR “Hypertension, Pregnancy-Induced”[Mesh] OR “Pre-Eclamp*”[tiab] OR preeclamp*[tiab] OR Eclamp*[tiab]
#2 | Dietary Patterns | (“dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “diet variety”[tiab] OR “dietary variety”[tiab] OR “varied diet”[tiab] OR “dietary guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary intake*”[tiab] OR “eating style*”[tiab] OR “Diet, Mediterranean”[Mesh] OR “Mediterranean Diet*”[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR “Dietary Approaches To Stop Hypertension Diet*”[tiab] OR “DASH diet*”[tiab] OR “Diet, Gluten-Free”[Mesh] OR “Gluten Free diet*”[tiab] OR “prudent diet*”[tiab] OR “Diet, Paleolithic”[Mesh] OR “Paleolithic Diet*”[tiab] OR “Diet, Vegetarian”[Mesh] OR “vegetarian diet*”[tiab] OR “vegan diet*”[tiab] OR “Diet, Healthy”[Mesh] OR “healthy diet*”[tiab] OR “plant based diet*”[tiab] OR “Diet, Western”[Mesh] OR “western diet*”[tiab] OR “Nordic Diet*”[tiab] OR “Okinawan diet*”[tiab] OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “high-fat diet*”[tiab] OR “low fat diet*”[tiab] OR “Diet, Sodium-Restricted”[Mesh] OR “low-sodium diet*”[tiab] OR “low salt diet*”[tiab] OR ((“Guideline Adherence”[Mesh] OR “guideline adherence*”[tiab])AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR “diet score*”[tiab] OR “diet quality score*”[tiab] OR “diet quality index*”[tiab] OR kidmed[tiab] OR “diet index*”[tiab] OR “dietary index*”[tiab] OR “food score*”[tiab] OR MedDietScore[tiab] OR “healthy eating index”[tiab])
#3 | | #1 AND #2
#4 | Limiters | #3 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Language: English; Publication Date: Oct 21, 2019-May 31, 2023

[underlined: Database: Embase]

Provider: U.S. National Library of Medicine

Date(s) Searched: October 5, 2021 (initial search); October 5, 2021 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: October 21, 2019 – May 31, 2023

Table A 9 Search for Embase (Search B)

Search # | Concept | String
#1 | Cardiovascular diseases | ‘Cardiovascular Disease’/de OR ‘Heart Failure’/exp OR ‘heart muscle ischemia’/de OR ‘cerebrovascular accident’/exp OR ‘vein thrombosis’/exp OR ‘Blood Pressure’/de OR (‘Lipids’/exp AND ‘blood’:ab,ti) OR ‘high density lipoprotein cholesterol’/exp OR ‘low density lipoprotein cholesterol’/exp OR ‘hypertension’/exp OR ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease*’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR ‘stroke*’:ab,ti OR ‘angina’:ab,ti OR ‘heart attack*’:ab,ti OR ‘venous thrombosis’:ab,ti OR ‘hypertension’:ab,ti OR ‘high blood pressure’:ab,ti OR ‘HDL cholesterol’:ab,ti OR ‘LDL cholesterol’:ab,ti OR ‘total cholesterol’:ab,ti OR ‘blood cholesterol’:ab,ti OR ‘triglycerides’:ab,ti OR hypertensi*:ab,ti OR ‘Pre-Eclamp*’:ab,ti OR preeclamp*:ab,ti OR Eclamp*:ab,ti
#2 | Dietary Patterns | ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/exp OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein restriction’/exp OR ‘sodium restriction’/exp OR ‘nordic diet’/de OR ‘protein diet’/exp; OR ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality’:ab,ti OR ‘dietary quality’:ab,ti OR ‘diet variety’:ab,ti OR ‘dietary variety’:ab,ti OR ‘varied diet’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘Mediterranean Diet*’:ab,ti OR ‘Dietary Approaches To Stop Hypertension Diet*’:ab,ti OR ‘DASH diet*’:ab,ti OR ‘Gluten Free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘Paleolithic Diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘healthy diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘Nordic Diet*’:ab,ti OR ‘Okinawan Diet*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti OR ‘diet score*’:ab,ti OR ‘diet quality score*’:ab,ti OR ‘diet quality index*’:ab,ti OR kidmed:ab,ti OR ‘diet index*’:ab,ti OR ‘dietary index*’:ab,ti OR ‘food score*’:ab,ti OR MedDietScore:ab,ti OR ‘healthy eating index’:ab,ti; OR (‘guideline adherence*’ AND (diet OR dietary OR food OR beverage* OR nutrition*)):ab,ti
#3 | | #1 AND #2
#4 | Limiters | #3 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti) AND [2019-2023]/py

[underlined: Database: Cochrane Central Register of Controlled Trials (CENTRAL)]

Provider: U.S. National Library of Medicine

Date(s) Searched: October 5, 2021 (initial search); October 5, 2021 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: October 21, 2019 – May 31, 2023

Table A 10 Search for Cochrane CENTRAL (Search B)

Search # | Concept | String
#1 | Cardiovascular Diseases | [mh ^“Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Ischemia”] OR [mh “Stroke”] OR [mh “Venous Thrombosis”] OR [mh ^“Blood Pressure”] OR [mh “Lipids”/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh “Triglycerides”] OR [mh “Hypertension”] OR [mh “Hypertension, Pregnancy-Induced”] OR (“cardiovascular disease*” OR “coronary artery disease” OR “heart disease*” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR “stroke*” OR “angina” OR “heart attack*” OR “venous thrombosis” OR “hypertension” OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR “blood cholesterol” OR “triglycerides” OR hypertensi* OR “Pre-Eclamp*” OR preeclamp* OR Eclamp*):ti,ab,kw
#2 | Dietary Patterns | [mh “Diet, Mediterranean”] OR [mh “Dietary Approaches To Stop Hypertension”] OR [mh “Diet, Gluten-Free”] OR [mh “Diet, Paleolithic”] OR [mh “Diet, Vegetarian”] OR [mh “Diet, Healthy”] OR [mh “Diet, Western”] OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, Sodium-Restricted”] OR [mh “Guideline Adherence”]; OR (“dietary pattern” OR “dietary patterns” OR “diet pattern” OR “diet patterns” OR “eating pattern” OR “eating patterns” OR “food pattern” OR “food patterns” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline” OR “dietary guidelines” OR “dietary recommendation” OR “dietary recommendations” OR “dietary intake” OR “dietary intakes” OR “eating style” OR “eating styles” OR “Mediterranean Diet” OR “Mediterranean Diets” OR “Dietary Approaches To Stop Hypertension Diet” OR “Dietary Approaches To Stop Hypertension Diets” OR “DASH diet” OR “DASH diets” OR “Gluten Free diet” OR “Gluten Free diets” OR “prudent diet” OR “prudent diets” OR “Paleolithic Diet” OR “Paleolithic Diets” OR “vegetarian diet” OR “vegetarian diets” OR “vegan diet” OR “vegan diets” OR “healthy diet” OR “healthy diets” OR “plant based diet” OR “plant based diets” OR “Western diet” OR “Western diets” OR “Nordic Diet” OR “Nordic Diets” OR “Okinawan Diet” OR “Okinawan Diets” OR “high-fat diet” OR “high-fat diets” OR “low fat diet” OR “low fat diets” OR “low-sodium diet” OR “low-sodium diets” OR “low salt diet” OR “low salt diets” OR “diet score” OR “diet scores” OR “diet quality score” OR “diet quality scores” OR “diet quality index” OR “diet quality indexes” OR “diet quality indices” OR kidmed OR “diet index” OR “diet indexes” OR “diet indices” OR “dietary index” OR “dietary indexes” OR “dietary indices” OR “food score” OR “food scores” OR MedDietScore OR “healthy eating index” OR “healthy eating indexes” OR “healthy eating indices”):ti,ab,kw; OR (“guideline adherence” NEAR/2 (diet OR dietary OR food OR beverage* OR nutrition*)):ti,ab,kw
#3 | | #1 AND #2; In Trials (Word variations have been searched); year first published 2019–2023

[underlined: Database: CINAHL]

Provider: U.S. National Library of Medicine

Date(s) Searched: October 5, 2021 (initial search); October 5, 2021 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: October 21, 2019 – May 31, 2023

Table A 11 Search for CINAHL (Search B)

Search # | Concept | String
#1 | Cardiovascular diseases | (MH “Cardiovascular Diseases”) OR (MH “Heart Failure+”) OR (MH “Myocardial Ischemia+”) OR (MH “Stroke+”) OR (MH “Venous Thrombosis+”) OR (MH “Blood Pressure”) OR (MH “Lipids+/BL”) OR (MH “Lipoproteins, HDL Cholesterol”) OR (MH “Lipoproteins, LDL Cholesterol”) OR (MH Triglycerides) OR (MH Hypertension) OR (TI “cardiovascular disease*” OR “coronary artery disease” OR “heart disease*” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR “stroke*” OR “angina” OR “heart attack*” OR “venous thrombosis” OR “hypertension” OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR “blood cholesterol” OR “triglycerides” OR hypertensi* OR “Pre-Eclamp*” OR preeclamp* OR Eclamp*) OR (AB “cardiovascular disease*” OR “coronary artery disease” OR “heart disease*” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR “stroke*” OR “angina” OR “heart attack*” OR “venous thrombosis” OR “hypertension” OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR “blood cholesterol” OR “triglycerides” OR hypertensi* OR “Pre-Eclamp*” OR preeclamp* OR Eclamp*)
#2 | Dietary Patterns | (MH “Mediterranean Diet”) OR (MH “DASH Diet”) OR (MH “Diet, Gluten-Free”) OR (MH “Diet, Paleolithic”) OR (MH “Vegetarianism”) OR (MH “Diet, Western”) OR (MH “Diet, Fat-Restricted”) OR (MH “Diet, Sodium-Restricted”) OR (MH “Restricted Diet”) OR (MH “Diet, High Protein”) OR (MH “Diet, Nordic”) OR (MH “Plant-Based Diet”); OR (TI “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “Okinawan diet” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet*” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*” OR “low fat diet*” OR “low-sodium diet*” OR “low salt diet*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index”) OR (AB “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “Okinawan diet” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet*” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*” OR “low fat diet*” OR “low-sodium diet*” OR “low salt diet*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index”); OR ((MH “Guideline Adherence”) OR (TI “guideline adherence*”) OR (AB “guideline adherence*”)) AND ((TI diet OR dietary OR food OR beverage* OR nutrition*) OR (AB diet OR dietary OR food OR beverage* OR nutrition*))
#3 | | #1 AND #2
#4 | Limiters | #3 NOT ((MH “Animals+”) OR (MH “Animal Studies”)); NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication”)); English, Apply equivalent subjects; Published Date: October 2019 – September 2023