# Appendix 2 Conclusion statements from the existing systematic review

Table A 2 Conclusion statements from the existing systematic review for the research question: What is the relationship between dietary patterns consumed during pregnancy and risk of hypertensive disorders of pregnancy?

Citation | Conclusion statement and grade
Raghavan R, Dreibelbis C, Kingshipp BJ, Wong, YP, Terry N, Abrams B, Bartholomew A, Bodnar LM, Gernand A, Rasmussen K, Siega-Riz AM, Stang JS, Casavale KO, Spahn JM, Stoody E. Dietary Patterns before and during Pregnancy and Risk of Hypertensive Disorders of Pregnancy: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0101 | Limited evidence in healthy Caucasian women with access to health care suggests that dietary patterns before and during pregnancy higher in vegetables, fruits, whole grains, nuts, legumes, fish, and vegetable oils and lower in meat and refined grains are associated with a reduced risk of hypertensive disorders of pregnancy, including preeclampsia and gestational hypertension. Not all components of the assessed dietary patterns were associated with all hypertensive disorders. (Grade: Limited); Evidence is insufficient to estimate the association between dietary patterns before and during pregnancy and risk of hypertensive disorders of pregnancy in minority women and those of lower socioeconomic status.