# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
DASH: Dietary Approaches to Stop Hypertension
DM: Diabetes mellitus
DP: Dietary pattern
EVOO: Extra virgin olive oil
FBG: Fasting blood glucose
FFQ: Food frequency questionnaire
GDM: Gestational diabetes mellitus
GW: Gestational weeks
HDI: Human Development Index
HDP: Hypertensive disorders of pregnancy
HELLP: Hemolysis, Elevated Liver enzymes and Low Platelets
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NICHD: Eunice Kennedy Shriver National Institute of Child Health and Development
NRCT: Non-randomized controlled trial
PCS: Prospective cohort study
RCT: Randomized controlled trial
SEP: Socioeconomic position
SES: Socioeconomic status
TFD: Three-day food diary
USDA: United States Department of Agriculture