# References of the articles included in the systematic review

1 Angali KA, Shahri P, Borazjani F. Maternal dietary pattern in early pregnancy is associated with gestational weight gain and hyperglycemia: A cohort study in South West of Iran. Diabetes Metab Syndr. 2020;14(16):1711–1717. doi:10.1016/j.dsx.2020.08.008 32916554
2 Assaf-Balut C, García de la Torre N, Fuentes M, A High Adherence to Six Food Targets of the Mediterranean Diet in the Late First Trimester is Associated with a Reduction in the Risk of Materno-Foetal Outcomes: The St. Carlos Gestational Diabetes Mellitus Prevention Study. Nutrients. 2018;11(1):66. doi:10.3390/nu11010066 30602688
3 Badon S, Enquobahrie DA, Wartko PD, Healthy Lifestyle During Early Pregnancy and Risk of Gestational Diabetes Mellitus. Am J Epidemiol. 2017;186(3):326–333. doi:10.1093/aje/kwx095 28481961
4 Bernier E, Plante AS, Robitaille J, First-trimester diet quality in association with maternal subcutaneous and visceral adipose tissue thicknesses and glucose homeostasis during pregnancy. Int J Food Sci Nutr. 2023;74(2):268–287. doi:10.1080/09637486.2023.2171371 36710410
5 de Seymour JV, Beck KL, Conlon CA, An Investigation of the Relationship Between Dietary Patterns in Early Pregnancy and Maternal/Infant Health Outcomes in a Chinese Cohort. Front Nutr. 2022;9:775557. doi:10.3389/fnut.2022.775557 35529458
6 Ding Y, Xu F, Zhong C, Association between Chinese Dietary Guidelines Compliance Index for Pregnant Women and Risks of Pregnancy Complications in the Tongji Maternal and Child Health Cohort. Nutrients. 2021;13(3):829. doi:10.3390/nu13030829 33802324
7 Du HY, Jiang H, O K, Association of Dietary Pattern during Pregnancy and Gestational Diabetes Mellitus: A Prospective Cohort Study in Northern China. Biomed Environ Sci. 2017;30(12):887–897. doi:10.3967/bes2017.119 29335058
8 Flor-Alemany M, Acosta P, Marín-Jiménez N, Baena-García L, Aranda P, Aparicio VA. Influence of the degree of adherence to the mediterranean diet and its components on cardiometabolic risk during pregnancy. The GESTAFIT project. Nutr Metab Cardiovasc Dis. 2021;31(8):2311–2318. doi:10.1016/j.numecd.2021.04.019 34112581
9 Flor-Alemany M, Acosta-Manzano P, Migueles J, Baena-García L, Aranda P, Aparicio V. Association of Mediterranean diet adherence during pregnancy with maternal and neonatal lipid, glycemic and inflammatory markers: The GESTAFIT project. Matern Child Nutr. 2023;19:e13454. doi:10.1111/mcn.13454 36437523
10 Flynn AC, Seed PT, Patel N, Dietary patterns in obese pregnant women; influence of a behavioral intervention of diet and physical activity in the UPBEAT randomized controlled trial. Int J Behav Nutr Phys Act. 2016;13(1):124. doi:10.1186/s12966-016-0450-2 27894316
11 Fulay AP, Rifas-Shiman SL, Oken E, Perng W. Associations of the dietary approaches to stop hypertension (DASH) diet with pregnancy complications in Project Viva. Eur J Clin Nutr. 2018;72(10):1385–1395. doi:10.1038/s41430-017-0068-8 29339829
12 Hajianfar H, Esmaillzadeh A, Feizi A, Shahshahan Z, Azadbakht L. The Association Between Major Dietary Patterns and Pregnancy-related Complications. Arch Iran Med. 2018;21(10):443–451.30415552
13 He JR, Yuan MY, Chen NN, Maternal dietary patterns and gestational diabetes mellitus: a large prospective cohort study in China. Br J Nutr. 2015;113(8):1292–1300. doi:10.1017/S0007114515000707 25821944
14 Hehua Z, Yang X, Qing C, Shanyan G, Yuhong Z. Dietary patterns and associations between air pollution and gestational diabetes mellitus. Environ Int. 2021;147:106347. doi:10.1016/j.envint.2020.106347 33385926
15 Hillesund ER, Bere E, Sagedal LR, Pre-pregnancy and early pregnancy dietary behavior in relation to maternal and newborn health in the Norwegian Fit for Delivery study - a post hoc observational analysis. Food Nutr Res. 2018;62(1654-661X (Print))doi:10.29219/fnr.v62.1273
16 Hrolfsdottir L, Gunnarsdottir I, Birgisdottir BE, Can a Simple Dietary Screening in Early Pregnancy Identify Dietary Habits Associated with Gestational Diabetes? Nutrients. 2019;11(8):1868. doi:10.3390/nu11081868 31405206
17 Hu J, Oken E, Aris I, Dietary Patterns during Pregnancy Are Associated with the Risk of Gestational Diabetes Mellitus: Evidence from a Chinese Prospective Birth Cohort Study. Nutrients. 2019;11(2):405. doi:10.3390/nu11020405 30769927
18 Karamanos B, Thanopoulou A, Anastasiou E, Relation of the Mediterranean diet with the incidence of gestational diabetes. Eur J Clin Nutr. 2014;68(1):8–13. doi:10.1038/ejcn.2013.177 24084515
19 Li M, Grewal J, Hinkle SN, Healthy dietary patterns and common pregnancy complications: a prospective and longitudinal study. Am J Clin Nutr. 2021;114(3):1229–1237. doi:10.1093/ajcn/nqab145 34075392
20 Lindsay KL, Buss C, Wadhwa PD, Entringer S. The Effect of a Maternal Mediterranean Diet in Pregnancy on Insulin Resistance is Moderated by Maternal Negative Affect. Nutrients. 2020;12(2):420. doi:10.3390/nu12020420 32041106
21 Lindsay KL, Milone GF, Grobman WA, Periconceptional diet quality is associated with gestational diabetes risk and glucose concentrations among nulliparous gravidas. Front Endocrinol. 2022;13:940870. doi:10.3389/fendo.2022.940870
22 Mak JKL, Pham NM, Lee AH, Dietary patterns during pregnancy and risk of gestational diabetes: a prospective cohort study in Western China. Nutr J. 2018;17(1):107. doi:10.1186/s12937-018-0413-3 30454043
23 Makarem N, Chau K, Miller EC, Association of a Mediterranean Diet Pattern With Adverse Pregnancy Outcomes Among US Women. JAMA Netw Open. 2022;5(12):e2248165. doi:10.1001/jamanetworkopen.2022.48165 36547978
24 Meinila J, Valkama A, Koivusalo SB, Association between diet quality measured by the Healthy Food Intake Index and later risk of gestational diabetes-a secondary analysis of the RADIEL trial. Eur J Clin Nutr. 2017;71(4):555–557. doi:10.1038/ejcn.2016.275 28145421
25 Miele M, Souza R, Calderon IM, Maternal Nutrition Status Associated with Pregnancy-Related Adverse Outcomes. Nutrients. 2021;13(7):2398. doi:10.3390/nu13072398 34371906
26 Pajunen L, Korkalo L, Koivuniemi E, A healthy dietary pattern with a low inflammatory potential reduces the risk of gestational diabetes mellitus. Eur J Nutr. 2022;61(3):1477–1490. doi:10.1007/s00394-021-02749-z 34846602
27 Paknahad ZA-O, Fallah A, Moravejolahkami AR. Maternal Dietary Patterns and Their Association with Pregnancy Outcomes. Clin Nutr Res. 2019;8(1):64–73. doi:10.7762/cnr.2019.8.1.64 30746349
28 Radesky JS, E. O, Rifas-Shiman SL, Kleinman KP, Rich-Edwards JW, Gillman MW. Diet during early pregnancy and development of gestational diabetes. Paediatr Perinat Epidemiol. 2008;22(1):47–59. doi:10.1111/j.1365-3016.2007.00899.x 18173784
29 Rifas-Shiman SL, W. R-EJ, Kleinman KP, Oken E, Gillman MW. Dietary quality during pregnancy varies by maternal characteristics in Project Viva: a US cohort. J Am Diet Assoc. 2009;109(6):1004–1011. doi:10.1016/j.jada.2009.03.001 19465182
30 Sauder KA, Starling AP, Shapiro AL, Diet, physical activity and mental health status are associated with dysglycaemia in pregnancy: the Healthy Start Study. Diabet Med. 2016;33(5):663–667. doi:10.1111/dme.13093 26872289
31 Tranidou A, Dagklis T, Magriplis E, Pre-Pregnancy Adherence to Mediterranean Diet and Risk of Gestational Diabetes Mellitus: A Prospective Cohort Study in Greece. Nutrients. 2023;15(4):848. doi:10.3390/nu15040848 36839206
32 Tryggvadottir EA, Medek H, Birgisdottir BE, Geirsson RT, Gunnarsdottir I. Association between healthy maternal dietary pattern and risk for gestational diabetes mellitus. Eur J Clin Nutr. 2016;70(2):237–242. doi:10.1038/ejcn.2015.145 26350393
33 Wang H, Huang L, Lin L, The overall plant-based diet index during pregnancy and risk of gestational diabetes mellitus: a prospective cohort study in China. Br J Nutr. 2021;126(10):1519–1528. doi:10.1017/S0007114521000234 33468274
34 Yee LM, Silver RM, Haas DM, Quality of periconceptional dietary intake and maternal and neonatal outcomes. Am J Obstet Gynecol. 2020;223(1):121. doi:10.1016/j.ajog.2020.01.042
35 Yong H, Mohd Shariff Z, Mohd Yusof BN, The association between dietary patterns before and in early pregnancy and the risk of gestational diabetes mellitus (GDM): Data from the Malaysian SECOST cohort. PLoS One. 2020;15(1):e0227246. doi:10.1371/journal.pone.0227246 31923230
36 Zhou X, Chen R, Zhong C, Maternal dietary pattern characterised by high protein and low carbohydrate intake in pregnancy is associated with a higher risk of gestational diabetes mellitus in Chinese women: a prospective cohort study. Br J Nutr. 2018;120(9):1045–1055. doi:10.1017/S0007114518002453 30355392
37 Al Wattar BH, Dodds J, Placzek A, Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Med. 2019;16(7):e1002857. doi:10.1371/journal.pmed.1002857 31335871
38 Assaf-Balut C, García de la Torre N, Durán A, A Mediterranean diet with additional extra virgin olive oil and pistachios reduces the incidence of gestational diabetes mellitus (GDM): A randomized controlled trial: The St. Carlos GDM prevention study. PLoS One. 2017;12(10):e0185873. doi:10.1371/journal.pone.0185873 29049303
39 Assaf-Balut C, García de la Torre N, Duran A, A Mediterranean Diet with an Enhanced Consumption of Extra Virgin Olive Oil and Pistachios Improves Pregnancy Outcomes in Women Without Gestational Diabetes Mellitus: A Sub-Analysis of the St. Carlos Gestational Diabetes Mellitus Prevention Study. Ann Nutr Metab. 2019;74(1):69–79. doi:10.1159/000495793 30554220
40 Dodd J, Deussen A, Louise J. A Randomised Trial to Optimise Gestational Weight Gain and Improve Maternal and Infant Health Outcomes through Antenatal Dietary, Lifestyle and Exercise Advice: The OPTIMISE Randomised Trial. Nutrients. 2019;11(12):2911. doi:10.3390/nu11122911 31810217
41 Melero V, García de la Torre N, Assaf-Balut C, Effect of a Mediterranean Diet-Based Nutritional Intervention on the Risk of Developing Gestational Diabetes Mellitus and Other Maternal-Fetal Adverse Events in Hispanic Women Residents in Spain. Nutrients. 2020;12(11):3505. doi:10.3390/nu12113505 33202607
42 Papandreou P, Amerikanou C, Vezou C, Gioxari A, Kaliora AC, Skouroliakou M. Improving Adherence to the Mediterranean Diet in Early Pregnancy Using a Clinical Decision Support System; A Randomised Controlled Clinical Trial. Nutrients. 2023;15(5):432. doi:10.3390/nu15020432 36678303
43 Van Horn L, Peaceman A, Kwasny M, Dietary Approaches to Stop Hypertension Diet and Activity to Limit Gestational Weight: Maternal Offspring Metabolics Family Intervention Trial, a Technology Enhanced Randomized Trial. Am J Prev Med. 2018;55(5):603–614. doi:10.1016/j.amepre.2018.06.015 30262148
44 Zhao L, Zhang P, Zheng Q, Deka A, Choudhury R, Rastogi S. Does a MediDiet With Additional Extra Virgin Olive Oil and Pistachios Reduce the Incidence of Gestational Diabetes? Endocr Pract. 2022;28(2):135–141. doi:10.1016/j.eprac.2021.08.010 34481972
45 Ruiz-Gracia T, Duran A, Fuentes M, Lifestyle patterns in early pregnancy linked to gestational diabetes mellitus diagnoses when using IADPSG criteria. The St Carlos gestational study. Clin Nutr. 2016;35(3):699–705. doi:10.1016/j.clnu.2015.04.017 25998584