# Summary of conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question: “What is the relationship between dietary patterns consumed during pregnancy and risk of gestational diabetes mellitus?” with the following conclusion statement.^*^ The grade reflects the strength of the evidence underlying the conclusion statement.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

Dietary patterns consumed during pregnancy that are characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, whole grains, fish/seafood, and unsaturated fats, and lower intakes of red and processed meat, added sugars, and saturated fats are associated with lower risk of gestational diabetes mellitus. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

## Research recommendations

To more adequately assess the relationship between dietary patterns during pregnancy and risk of gestational diabetes mellitus, additional research is needed that should:

1. Include populations representative of all Americans, such as diversity in race and/or ethnicity, SEP, disability status, and gender identity. Of note, no included studies reported including American Indian or Alaska Native participants and a single study included Native Hawaiians.
2. Clearly describe characteristics related to health disparities (e.g., racial or ethnic group, religion, socioeconomic status, gender, age, or mental health; cognitive, sensory, or physical disability; sexual orientation or gender identity; geographic location; substance use; or other characteristics historically linked to discrimination or exclusion).
3. Conduct well-designed and sufficiently powered trials where the isolated effect of the dietary pattern on the outcome can be determined and where the dietary patterns are described in sufficient detail.
4. Administer dietary assessments as early as possible in and multiple times throughout pregnancy, use validated and reliable assessment methods, such as multiple 24 hour recalls and food frequency questionnaires validated for the population, and provide clear information on the period of time captured by the assessments.
5. Consider stratifying analyses by race and/or ethnicity or SEP (or other social determinants of health) or account for these and other key confounders in methods and/or analyses.
6. Include strong justification when controlling for variables that occur after the start of the exposure period (i.e., pregnancy) that could have been affected by the exposure, such as gestational weight gain.
7. Consider the severity of GDM (i.e., diet-managed GDM vs. insulin-treated GDM) in the study design and/or analytic plan.
8. In addition to other planned analyses, evaluate the dietary pattern against existing indices of dietary quality (e.g., Healthy Eating Index) to facilitate comparison across studies and carefully describe food groups in dietary patterns.
9. Describe carefully the criteria used for GDM diagnosis and provide sensitivity analyses using other GDM criteria to facilitate comparison across studies.
10. Collect information on prenatal supplementation, including nutrient types and amounts, and consider supplementation in study design and/or analytic plans.
11. Since practical considerations limit most studies on pregnancy to observational designs, detailed collection and reporting of characteristics, behaviors and their timing and accounting for these factors in the analysis is critical.

Table 7 Evidence examining the relationship between dietary patterns consumed during pregnancy and gestational diabetes mellitus^a^

Study Characteristics | Intervention or Exposure and Outcome | Results | Confounders, Funding, and Summary
RCT
Al Wattar, 2019^37^; RCT, Parallel-arm, United Kingdom, ESTEEM; Baseline N=1,252; Analytic N= 974 (Attrition: 22%); - Age (y): IG: 31.4±5.2^*^; CG: 30.9±5.2; ○ >40 (%): IG: 3.9; CG: 3.1; * Means or mean ± standard deviation unless otherwise specified; - Race/Ethnicity (%):; ○ Asian: IG: 43.4; CG: 44.1; ○ White: IG: 36.6; CG: 35.5; ○ Black: IG: 16.4; CG: 17.2; ○ Other: IG: 3.7; CG: 3.3; - Baseline BMI (%):; ○ 25-29.9: IG: 16.7; CG: 16.7; ○ ≥30: IG: 69.1; CG: 69.6; History of GDM (%): IG: 2.7; CG: 3.8 | IG vs. CG; 24h recall at baseline (~18 GW); ESTEEM Q at 20, 24, 28, 32, and 36 GW; DP Description:; - Control group (CG): Received usual care and antenatal dietary advice as per U.K. national recommendations; - Intervention group (IG): High intake of nuts, extra virgin olive oil, fruit, vegetables, non-refined grains, and legumes; moderate to high consumption of fish; low to moderate intake of poultry and dairy products; low consumption of red meat and processed meat; and avoidance of sugary drinks, fast food, and food rich in animal fat. Participants provided with 30 g/d of mixed nuts and 0.5 L/wk of EVOO.; Adherence: ESTEEM Q score did not differ between groups at baseline but was significantly higher in IG vs CG after the intervention.; - Positive components: Olive oil (as main fat and svg/d); Nuts (including peanuts) Vegetables; Fruit (including juice); Pulses; Fish or shellfish; White meat over red meat; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial sweets or pastries; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 75g OGTT: fasting ≥5.1 or 2h ≥8.5 mmol/l | GDM; Multivariable logistic regression; aOR (95% CI); [underlined: All participants:] 0.65 (0.47, 0.91), p=0.01; [underlined: BMI ≥30:] 0.58 (0.40, 0.86), p<0.05; [underlined: BMI <30:] 0.88 (0.47, 1.65), p≥0.05; p for interaction=0.27; [underlined: Raised TG:] 0.64 (0.39, 1.04), p≥0.05; [underlined: Normal TG:] 0.68 (0.41, 1.11), p≥0.05; p for interaction=0.86; [underlined: Chronic HTN:] 0.28 (0.07, 1.07), p≥0.05; [underlined: No chronic HTN:] 0.70 (0.50, 1.00), p≥0.05; p for interaction=0.19 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Family history of HDP, Family history of DM, History of stillbirth, Recruitment center; Funding: Barts Charity; California Walnut Commission and Blue Diamond Growers donated walnuts and almonds, respectively; Summary: A Mediterranean-style DP supplemented with mixed nuts and EVOO reduced risk of GDM compared to usual care in all metabolically at-risk participants and participants with BMI ≥30. There was no effect among participants with BMI <30, participants with normal and raised TG, and participants with or without chronic HTN.
Assaf-Balut, 2017^38^; RCT, Parallel-arm, Spain, The St. Carlos GDM Prevention Study; Baseline N=1000; Analytic N= 874 (Attrition: 13%); - Age (y): CG: 32.7±5.3; IG: 33.2±5.0; - Race/Ethnicity (%): White: CG: 67.8; IG: 69.0; Hispanic: CG: 28.4; IG: 28.6; Other: CG: 3.8; IG: 2.4; - SEP:; ○ Education (%): Elementary: CG: 10.8; IG: 6.8; University: CG: 50.2; IG: 50.4; ○ Employment (%): CG: 75.2; IG: 78.0; - Pre-pregnancy BMI: CG: 23.3±4.0; IG: 22.9±3.6; - History of GDM (%): CG: 2.8; IG: 2.8; - Smoking (%): CG: 8.0; IG: 8.6 | IG vs. CG Overall GDM; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between groups at baseline. Scores significantly increased over time in both groups, but scores remained significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcome and assessment methods:; Overall GDM assessed at: 24-28 GW; GDM diagnosed following 75g OGTT: fasting ≥92, 1h ≥180, or 2h ≥153 mg/dL | Overall GDM; Logistic regression; RR (95% CI); 0.75 (0.57, 0.98), p=0.039 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Family history of T2 DM
Assaf-Balut, 2017^38^ cont. | Outcome and assessment methods:; Insulin-treated GDM and OGTT assessed at: 24-28 GW; FBG assessed at: 36-38 GW; HbA1C and HOMA-IR assessed at: 24-28 GW and 36-38 GW; Insulin therapy initiated after GDM diagnosis when monitoring indicated >50% of fasting/pre-prandial BG >95 mg/dL or 1h postprandial BG >140 mg/dL Blood samples drawn after overnight fast. HOMA-IR used to calculate insulin resistance. | Insulin-treated GDM; Logistic regression; RR (95% CI); 0.44 (0.25, 0.81), p=0.008; OGTT; Student t test or Mann-Whitney U test Mean±SD, mg/dL; [underlined: FBG:] CG: 85.7±6.6; IG: 84.1±6.6, p=0.001; [underlined: 1h BG:] CG: 123.7±32.0; IG: 123.5±30.2, p=0.912; [underlined: 2h BG:] CG: 110.0±26.3; IG: 106.3±23.8, p=0.042; FBG; Student t test or Mann-Whitney U test Mean±SD, mg/dL; [underlined: 36-38 GW:] CG: 77.1±7.4; IG: 74±7.7, p=0.003; HbA1C; Student t test or Mann-Whitney U test Mean±SD, %; [underlined: 24-28 GW:] CG: 5.1±0.3; IG: 4.9±0.3, p=0.001; [underlined: 36-38 GW:] CG: 5.3±0.3; IG: 5.2±0.2, p=0.001; HOMA-IR; Student t test or Mann-Whitney U test Mean±SD; [underlined: 24-28 GW:] CG: 2.2±2.6; IG: 2.0±1.4, p=0.045; [underlined: 36-38 GW:] CG: 2.3±2.7; IG: 2.0±2.3, p=0.055 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Fondo Europeo de Desarrollo Regiona; Summary: A MedDiet supplemented with EVOO and pistachios reduced risk of both overall GDM and insulin-treated GDM, as well as lowered fasting blood glucose and HbA1C at both 24-28 GW and 36-38 GW, OGTT 2h BG, and insulin resistance at 24-28 GW, compared to lower alignment with a MedDiet. The intervention did not have an effect on OGTT 1h BG or insulin resistance at 36-38 GW.
Assaf-Balut, 2019^39^; RCT, Parallel-arm, Spain, The St. Carlos GDM Prevention Study; Baseline N=823; Analytic N= 697 (Attrition: 15%); - Age (y): CG: 32.5±5.3; IG: 32.9±4.9; - Race/Ethnicity (%): White: CG: 67.1; IG: 67.8; Hispanic: CG: 29.1; IG: 30.3; Other: CG: 3.9; IG: 1.9; - SEP:; ○ Education (%): Elementary: CG: 7.6; IG: 6.1; University: CG: 50.1; IG: 51.4; ○ Employment (%): CG: 75.3; IG: 79.2; - Pre-pregnancy BMI: CG: 22.9±3.8; IG: 22.4±3.3; - History of GDM (%): CG: 2.4; IG: 2.9; ○ Current GDM (%): 0.0; - Smoking (%): CG: 7.4; IG: 8.3 | IG vs. CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between groups at baseline. Scores significantly increased over time in both groups, but scores remained significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcome and assessment methods:; OGTT: 24-28 GW; HbA1C and HOMA-IR: 24-28 GW and 36-38 GW; Fasting glucose: 36-38 GW; 75 g OGTT. Blood samples drawn after overnight fast. Insulin resistance used to calculate HOMA-IR. | OGTT; Student t test or Mann-Whitney U test Mean diff (95% CI), mg/dL; [underlined: Fasting]: 1.4 (0.6, 2.4), p=0.001; [underlined: 1h BG]: −0.6 (−4.5, 3.3), p=0.754; [underlined: 2h BG]: 1.6 (−1.5, 4.6), p=0.313; HbA1C; Student t test or Mann-Whitney U test Mean diff (95% CI), %; [underlined: 24-28 GW]: 0.09 (0.05, 0.15), p=0.000; [underlined: 36-38 GW]: 0.1 (0.0, 0.2), p=0.002; FBG; Student t test or Mann-Whitney U test Mean diff (95% CI), mg/dL; [underlined: 36-38 GW]: 2.1 (0.5, 3.6), p=0.009; HOMA-IR; Student t test or Mann-Whitney U test Mean diff (95% CI); [underlined: 24-28 GW]: 0.1 (−0.1, 0.3), p=0.395; [underlined: 36-38 GW]: 0.1 (−0.4, 0.7), p=0.655 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Among normoglycemic participants, a MedDiet supplemented with EVOO and pistachios lowered fasting blood glucose and HbA1C at both 24-28 GW and 36-38 GW compared to lower alignment with a MedDiet. The intervention had no significant effect on OGTT 1h or 2h blood glucose or insulin resistance at either 24-28 GW or 36-38 GW.
Dodd, 2019^40^; RCT, Parallel-arm, Australia, OPTIMISE; Baseline N=641; Analytic N= 629 (Attrition: 2%); - Age (y): 31.53±4.76; - Race/Ethnicity (%): White: 67.46; Asian: 15.01; Indian, Pakistani, Sri Lankan: 8.06; Other: 9.47; - SEP:; ○ SEIFA IRSD (%): Quintile 1 (most disadvantaged): 16.75; Quintile 5: 17.85; - Baseline BMI: Median (IQR): 22.20 (20.87, 23.60); - Smoking (%): 4.42 | LI vs. SC; FFQ at: trial entry (10-20 GW), 28 GW, and 36 GW; DP Description:; - Lifestyle Intervention (LI): Received 3 in-person visits and 3 phone calls with dietitian or research assistant at trial entry, and 20, 24, 28, 32, and 36 GW. Dietary advice was consistent with current Australian dietary standards, maintaining a balance of carbohydrates, fat, and protein, and encouraging reduced intake of energy dense and non-core foods high in refined carbohydrates and saturated fats. Participants were advised to increase their intake of fiber, and to consume 2 svg/d fruit, 5 svg/d vegetables and 3 svg/d dairy.; - Standard Care (SC): Received antenatal care according to hospital guidelines, which did not include information relating to dietary intake, physical activity or weight gain during pregnancy.; Adherence: HEI scores did not differ at baseline but were higher in LI at 28 GW and 36 GW. Physical activity scores did not differ at either follow-up.; Outcome and assessment methods:; GDM assessed at: ~28 GW; Diagnosed following 75g OGTT: During the course of the trial, diagnostic criteria changed across the state from fasting >5.5 or 2h ≥7.8 mmol/L, to fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/L | GDM; Log Poisson Regression; OR (95% CI); 1.02 (0.66, 1.59), p=0.929 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Funding: The University of Adelaide; Lloyd Cox Strategic Research Excellence Award; NHMRC Practitioner Fellowship; Summary: A lifestyle intervention with dietary advice consistent with Australian dietary standards did not have an effect on risk of GDM compared to standard care.
Melero, 2020^41^; RCT, Parallel-arm, Spain, St. Carlos GDM prevention study; Baseline N=285; Analytic N= 260 (Attrition: 9%); - Age (y): CG: 31.3±5.6; IG: 31.7±5.4; - Race/Ethnicity (%): Hispanic: 100; - SEP:; ○ Education (%): Elementary: CG: 19.7; IG: 12.6; University: CG: 31.7; IG: 40.6; Unknown: CG: 1.4; IG: 0.7; ○ Unemployed (%): CG: 69.0; IG: 67.8; - Pre-pregnancy BMI: CG: 24.4±4.0; IG: 24.1±3.4; - History of GDM (%): CG: 4.9; IG: 2.8; - Smoking (%): CG: 0.7; IG: 0.7 | IG vs. CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg legumes/wk, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk >30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25-30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12-14 GW and 24-28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between the groups at baseline. Scores significantly increased over time in the IG, while no changes in the CG were observed. Scores remaining significantly higher in the IG compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; - Negative components: commercial pastries; red meat or sausages; animal fat; sugar-sweetened beverages; - Alcohol and fruit (including juice) components excluded; Outcome and assessment methods:; GDM and OGTT assessed at: 24-28 GW; HbA1C and insulin resistance assessed at: 24-28 GW and 36-38 GW; FBG assessed at: 36-38 GW; GDM diagnosed following 75 g OGTT: fasting ≥92 mg/dL, 1h ≥180/dL, or 2h ≥153 mg/dL; Blood samples drawn after 8-10 h fast. High HbA1C: >5.5%. HOMA-IR used to calculate insulin resistance. | GDM; Logistic regression; RR (95% CI); IG vs CG: 0.72 (0.50, 0.97), p=0.037; OGTT; Logistic regression; RR (95% CI); [underlined: FBG ≥92 mg/dL]: IG vs CG: 0.81 (0.55, 1.19), p=0.308; [underlined: 1h BG ≥180 mg/dL]: IG vs CG: 0.50 (0.15, 1.66), p=0.281; [underlined: 2h BG ≥153 mg/dL]: IG vs CG: 0.60 (0.27, 1.38), p=0.253; High HbA1C; Logistic regression; RR (95% CI); IG vs CG: 0.49 (0.33, 075), p=0.003; FBG; Student’s t test or the Mann–Whitney U test; Mean±SD, mg/dL; [underlined: 36-38 GW]: CG: 78.4±9.4; IG: 74.8±4.4, p=0.006; HOMA-IR; Student’s t test or the Mann–Whitney U test; Mean±SD; [underlined: 24-28 GW]: CG: 2.4±1.4; IG: 2.0±1.0, p=0.045; [underlined: 36-38 GW]: CG: 2.6±4.3; IG: 2.2±2.3, p=0.050 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Among Hispanic participants, a MedDiet supplemented with EVOO and pistachios (IG) reduced risk of GDM and high HbA1C compared to lower alignment with a MedDiet (CG). All OGTT comparisons were not significantly different. IG lowered FBG at 36-38 GW and insulin resistance at 24-28 GW compared to CG; the relationship between IG and insulin resistance at 36-38 GW neared significance.
Papandreou, 2023^42^; RCT, Parallel-arm, Greece, IASO Maternity Hospital; Baseline N=40; Analytic N= 40 (Attrition: 0%); - Age (y): 30.8±6.4; - SEP:; ○ Profession (%): Private sector: 32.5; State employee: 10.0; Homemaker: 35.0; Other: 22.5; - Pre-pregnancy BMI: (%): 25-29.9: 12.5; >30: 0.0; - History of GDM (%): DM before enrollment: 0.0; - Smoking (%): Before pregnancy: 25.0; During pregnancy: 7.5 | CDSS vs. CG; FFQ at: Baseline (TM1) and follow-up (3mo after baseline); DP Description:; - Clinical Decision Support System (CDSS) group: Received daily diet plans personalized to their needs, habits, and preferences, based on the MD, generated by CDSS software, renewed every 15 d, and paired w/ recommendations in line w/ the “National Dietary Guidelines for Pregnancy.”; - Control group (CG): Received general lifestyle guidelines based on the “National Dietary Guidelines for Pregnancy” through phone calls w/ the dietitians every 15 d.; Adherence: MedDietScore was higher in the CDSS group at both baseline and follow-up, but the MedDietScore increased more over follow-up in the CDSS group compared to the CG.; - Positive components: Vegetables; potatoes; legumes; fruit; whole grains; fish; olive oil; - Negative components: Red and processed meat; poultry; full-fat dairy; alcohol; Outcome and assessment methods:; FBG assessed at: Baseline (TM1) and follow-up (3mo after baseline); Blood drawn after overnight fast. | FBG; Paired-samples t-test or Wilcoxon signed-rank test; Mean±SD, mg/dL; [underlined: CDSS:] Baseline: 101.3±6.8; Follow-Up: 95.2±4.8, p<0.001; [underlined: CG:] Baseline: 97.1±21.3; Follow-Up: 95.4±20.1, p=0.212; Repeated measures ANOVA Between-subjects effect of treatment: p=0.679 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Funding: None; Summary: A personalized daily dietary plan based on the MD that was generated by the CDSS software reduced FBG from baseline to follow-up but did not have a statistically-significant effect over time compared to standard care.
Van Horn, 2018^43^; RCT, Parallel-arm, United States, MOMFIT; Baseline N=281; Analytic N= 194 (Attrition: 31%); - Age (y): MAMA-DASH: 33±4; UC: 34±4; - Race/Ethnicity (%): White: MAMA-DASH: 56.4; UC: 70.2; Black or African American: MAMA-DASH: 24.3; UC: 14.2; Other: MAMA-DASH: 19.3; UC: 15.6 Hispanic: MAMA-DASH: 21.4; UC: 21.3; - SEP:; ○ Total family income (%): <$20,000: MAMA-DASH: 3.6; UC: 5.7; $20,000−$49,999: MAMA-DASH: 12.4; UC: 13.5; ≥$200,000: MAMA-DASH: 16.1; UC: 19.2; ○ Education (%): ≤High school diploma/GED: MAMA-DASH: 4.3; UC: 5.0; Postgraduate work: MAMA-DASH: 47.5; UC: 33.3; - Pre-pregnancy BMI (%): ≥30: MAMA-DASH: 55.0; UC: 54.6; - DM or HbA1c >6.5% prior to enrollment (%): 0.0; - Smoking (%): 0.0 | MAMA-DASH vs. UC; 24 HR at: 15 GW and 35 GW; DP Description:; - MAMA-DASH: Higher low-fat milk and dairy products, fish, skinless poultry, lean meat and vegetable protein, unsaturated fats, fiber-rich whole grains, fruits, vegetables, and legumes encouraged. Lower sugar-sweetened beverages, other sweets, and non-nutrient-dense snack foods was discouraged. Caloric restriction to meet GWG, following nutrition guidelines for pregnant women, including avoidance of fish considered higher in mercury, inclusion of calcium-rich, vitamin D−enriched dairy, or calcium-fortified non-dairy products; Individual and group diet & PA counseling sessions; - Usual care (UC): Received usual-care, including biweekly newsletters and publicly available maternity website links via email; Adherence: No differences in diet scores between groups at baseline. Dixon DASH, Fung DASH, and HEI-2010 diet scores were higher in the MAMA-DASH vs UC group at 35 GW. Physical activity scores did not differ between groups.; - DASH positive components: Vegetables (not potatoes); nuts and legumes; fruit (including fruit juice); whole grains; low-fat dairy; - DASH negative components: Red and processed meat; sweetened beverages; sodium; Outcome and assessment methods:; FBG, insulin resistance assessed at: 15 GW and 35 GW; FBG methods NR. Insulin resistance calculated using HOMA-IR. | FBG; t-test of log-transformed mean changes Median (IQR), mg/dL; [underlined: MAMA-DASH:] Baseline: 86 (82, 90); 35 GW: 84 (80, 89); [underlined: UC:] Baseline: 87 (83, 91); 35 GW: 85 (81, 89); p=0.89; HOMA-IR; t-test of log-transformed mean changes Median (IQR); [underlined: MAMA-DASH:] Baseline: 1.2 (0.9, 1.7); 35 GW: 1.6 (1.3, 2.4); [underlined: UC:] Baseline: 1.3 (0.9, 1.8); 35 GW: 2.0 (1.4, 2.6); p=0.26 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Funding: NIDDK, NHLBI; NICHD; NCCIH; ORWH; OBSSR; the Indian Health Service; Summary: Among participants with pre-pregnancy BMI ≥25, a calorie-controlled, DASH-type diet and lifestyle intervention had no effect on FBG or insulin resistance at 35 GW.
Zhao, 2022^44^; RCT, Parallel-arm, China, Henan Provincial People’s Hospital; Baseline N=560; Analytic N= 500 Total Baseline N=560 (Attrition: 11%); - Age (y): CG: 28±5.2; IG: 29.4±5.6; - SEP:; ○ Employed (%): CG: 75.2; IG: 46.4; ○ Education (%): High school: CG: 0.1; IG: 10.8; University: CG: 37.2; IG: 38.8; Unknown: CG: 6.4; IG: 1.2; - Pre-pregnancy BMI: CG: 23.3±3.9; IG: 22.8±3.4; - History of GDM (%): CG: 2.8; IG: 2.8; - Smoking (%): Current: CG: 2.4; IG: 2 | IG vs. CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - Both groups: MedDiet (vegetables, fruits, skimmed dairy foods, whole grain cereals, legumes, fish; avoid refined grains, baked goods, soft drinks, juices, junk food, precooked meat, pre-sliced slices of bread) and walking 30 min/d recommended; - Intervention group (IG): Recommended to consume ≥40 ml/d EVOO and 25-30 g/d roasted pistachios recommended; Weekly visits with a dietitian; - Control group (CG): Recommended to restrict dietary fat, including extra virgin coconut oil and dry fruits, by the midwives.; Adherence: MEDAS scores did not differ at baseline. Scores significantly increased over time in both groups, but the IG had significantly higher scores than the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: Olive oil (as main fat and svg/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; - Negative components: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries; Outcome and assessment methods:; GDM assessed at: 24-28 GW; FBG, HbA1C, insulin resistance assessed at: 24-28 GW and 36-38 GW; GDM diagnosed following 75g OGTT: fasting ≥92, 1h ≥180/dL, or 2h ≥153 mg/dL; Blood samples drawn after overnight fast. HOMA-IR used to calculate insulin resistance. | GDM; Multivariate analysis; RR (CI); 0.74 (0.49, 0.99), p=0.02; FBG; t-test, mg/dL; [underlined: 24-28 GW:] IG: 90.8±6.1; CG: 92.3±5.6, p=0.004; [underlined: 36-38 GW]: IG: 73.7±7.4; CG: 76.2±7.8, p=0.0003; HbA1c; t-test, %; [underlined: 24-28 GW:] IG: 4.8±0.2; CG: 5.0±0.2, p<0.001; [underlined: 36-38 GW:] IG: 5.1±0.1; CG: 5.2±0.1, p<0.001; HOMA-IR; t-test; [underlined: 24-28 GW:] IG: 1.9±1.5; CG: 2.1±2.4, p=0.264; [underlined: 36-38 GW:] IG: 2.1±1.8; CG: 2.4±2.6, p=0.1342 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Family history; Funding: None; Summary: A MedDiet with recommended additional EVOO and pistachios reduced risk of GDM, as well as lowered fasting blood glucose and HbA1C at both 24-28 GW and 36-38 GW, compared to lower alignment with a MedDiet. The intervention did not have an effect on insulin resistance at 24-28 GW or 36-38 GW.
NRCT
Melero, 2020^41^; NRCT, Spain, St. Carlos GDM prevention study; Baseline N=458; Analytic N=412 (Attrition: 10%); - Age (y): CG: 31.3±5.6; RW: 31.4±5.7; - Race/Ethnicity (%): Hispanic: 100; - SEP:; ○ Education (%): Elementary: CG: 19.7; RW: 11.2; University: CG: 31.7; RW: 35.5; Unknown: CG: 1.4; RW: 2.5; ○ Unemployed (%): CG: 69.0; RW: 73.3; - Pre-pregnancy BMI: CG: 24.4±4.0; RW: 23.4±3.6, p=0.033; - History of GDM (%): CG: 4.9; RW: 2.5; - Smoking (%): CG: 0.7; RW: 1.6 | RW vs. CG; FFQ at: 8-12 GW, 24-28 GW, and 36-38 GW; DP Description:; - The real world (RW) and control group (CG) were both given the same basic MedDiet recommendations: ≥2 svg/d vegetables, ≥3 svg/d fruit (avoiding juices), 3 svg/d skimmed dairy products, wholegrain cereals, 2-3 svg/wk legumes, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals.; - RW recommended to consume ≥40 mL/d of EVOO and nuts ≥3d/wk.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ between the groups at baseline. Scores significantly increased over time in the RW, while no changes in the CG were observed. Scores remaining significantly higher in the RW compared to the CG at both 24-28 GW and 36-38 GW. Physical activity scores did not differ at either follow-up point.; - Positive components: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; - Negative components: commercial pastries; red meat or sausages; animal fat; sugar-sweetened beverages; - Alcohol and fruit (including juice) components excluded; Outcome and assessment methods:; GDM and OGTT assessed at: 24-28 GW; HbA1C assessed at: 24-28 GW and 36-38 GW; Blood samples drawn after 8-10 hr fast.; GDM diagnosed following 75g OGTT: fasting ≥92 mg/dL, 1h ≥180/dL, or 2h ≥153 mg/dL; High HbA1C defined as >5.5% | GDM; Logistic regression; RR (95% CI); RW vs CG: 0.77 (0.61, 0.97), p=0.008; OGTT; Logistic regression; RR (95% CI); [underlined: Fasting ≥92 mg/dL]: RW vs CG: 0.79 (0.61, 1.03), p=0.058; [underlined: 1h ≥180 mg/dL]: RW vs CG: 0.60 (0.28, 1.28), p=0.092; [underlined: 2h ≥153 mg/dL:] RW vs CG: 0.53 (0.26, 1.00), p=0.019; High HbA1C; Logistic regression; RR (95% CI); RW vs CG: 0.44 (0.22, 0.87), p=0.024 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM
Melero, 2020^41^ cont. | Outcome and assessment methods:; Insulin resistance assessed at: 24-28 GW and 36-38 GW; FBG assessed at: 36-38 GW; Blood samples drawn after 8-10 h fast. HOMA-IR used to calculate insulin resistance. | FBG; Student’s t test or the Mann–Whitney U test; Mean±SD, mg/dL; [underlined: 36-38 GW]: CG: 78.4±9.4; RW: 79.5±10.8, p=0.495; HOMA-IR; Student’s t test or the Mann–Whitney U test; Mean±SD; [underlined: 24-28 GW]: CG: 2.4±1.4; RW: 2.4±3.8, p=0.835; [underlined: 36-38 GW]: CG: 2.6±4.3; RW: 3.6±5.8, p=0.225 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Smoking, Parity, History of GDM; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Among Hispanic participants, a MedDiet in a real-world (RW) setting reduced risk of GDM and high HbA1C compared to lower alignment with a MedDiet in a trial setting (CG). In an OGTT, risk of 2h BG ≥153 mg/dL was lower in RW vs. CG, risk of FBG ≥92 mg/dL neared significance, and risk of 1h BG ≥180 mg/dL was not significant. RW did not have an effect on FBG at 36-38 GW or insulin resistance at either follow-up compared to CG.
Cohort Studies
Index/Score
Assaf-Balut, 2018^2^; PCS, Spain, St. Carlos GDM Prevention Study; Analytic N =874; - Age (y): Low: 31.2±6.0; High: 33.9±4.9, p=0.001; - Race/Ethnicity (%): White: Low: 58.1; High: 76.5; Hispanic: Low: 37.5; High: 18.3; Other: Low: 4.4; High: 5.2, p=0.005; - SEP:; ○ Education (%): Elementary: Low: 14.0; High: 4.3; University: Low: 47.8; High: 80.0, p=0.001; ○ Employment (%): 77.1; - Pre-pregnancy BMI: 23.1±3.8; - History of GDM (%): 2.9; - Smoking (%): 8.2 | Modified MEDAS (categorical alignment); FFQ at: 12-14 GW; DP Description:; - Positive components: EVOO (daily and weekly); Nuts; Vegetables; Whole fruits (excluding juice); - Negative component: Juice; - Low: meets 0-1 targets; Moderate: 2-4; High: 5-6; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 75g OGTT: fasting ≥92, 1h ≥180, or 2h ≥153 mg/dL | GDM; Multivariable logistic regression; OR (95% CI); [underlined: Pre-pregnancy BMI ≥25]; Moderate vs. Low (Ref): 0.31 (0.15, 0.64), p=0.002; High vs. Low (Ref): 0.04 (0.005, 0.342), p=0.003; [underlined: Pre-pregnancy BMI <25]; Moderate vs. Low (Ref): 0.69 (0.39, 1.24), p=0.214; High vs. Low (Ref): 0.65 (0.301, 1.400), p=0.271 | Key confounders accounted for:; Age, Physical activity, Pre-pregnancy BMI, Smoking, Parity, History of GDM
Assaf-Balut, 2018^2^ cont. | | GDM; Multivariable logistic regression; OR (95% CI); [underlined: Age ≥35y]; Moderate vs. Low (Ref): 0.62 (0.30, 1.25), p=0.179; High vs. Low (Ref): 0.24 (0.08, 0.68), p=0.008; [underlined: Age <35y]; Moderate vs. Low (Ref): 0.49 (0.29, 0.82), p=0.007; High vs. Low (Ref): 0.44 (0.19, 1.03), p=0.058 | Key confounders accounted for:; Age, Physical activity, Pre-pregnancy BMI, Smoking, History of GDM
Assaf-Balut, 2018^2^ cont. | | GDM; Multivariable logistic regression; OR (95% CI); [underlined: Multiparous]; Moderate vs. Low (Ref): 0.72 (0.41, 1.25), p=0.242; High vs. Low (Ref): 0.51 (0.22, 1.21), p=0.128; [underlined: Primiparous]; Moderate vs. Low (Ref): 0.38 (0.19, 0.73), p=0.003; High vs. Low (Ref): 0.20 (0.07, 0.56), p=0.002 | Key confounders accounted for:; Physical activity, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Funding: The Plan Nacional of I+D+D, AES 2013_2016; the Instituto de Salud Carlos III of Spain; the Fondo Europeo de Desarrollo Regional; the Sociedad de Endocrinología Nutrición y Diabetes de la Comunidad de Madrid; Summary: Greater alignment with the modified MEDAS was associated with reduced risk of GDM among participants with pre-pregnancy BMI ≥25 and who were primiparous. High alignment, but not moderate alignment, was associated with reduced risk of GDM among participants ≥35y when compared to low alignment. Moderate alignment was associated with reduced risk of GDM among participants <35y when compared to low alignment, while the high alignment association neared statistical significance. There was no association between the modified MEDAS and risk of GDM among participants with pre-pregnancy BMI <25 or who were multiparous.
Badon, 2017^3^; PCS, United States, Omega Study; Analytic N= ≥62 score: 611; <62 score: 2,444; - Age (y): 33±4.3; - Race/Ethnicity (%): White: 88.0; - SEP:; ○ Education (%): ≥High school: 98.0; - Pre-pregnancy BMI (%): 25-29.9: 16.0; ≥30: 7.0; - History of GDM (%): 1.0; - Smoking (%): 5.0 | AHEI-2010 (≥62 vs. <62 score); FFQ at: 15±3 GW; DP Description:; - Positive components: vegetables (not potatoes, French fries); fruit; legumes and nuts; whole grains; long-chain fats (EPA + DHA); PUFA; - Negative components: red and processed meat; SSB and fruit juice; trans FA; sodium; - Alcohol component excluded; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following failed 50g OGTT and follow-up 100g OGTT (≥2): fasting ≥105, 1h ≥190, 2h ≥165, 3h ≥145 mg/dL | GDM; Modified Poisson regression; RR (95% CI); 0.90 (0.59, 1.37), p≥0.05 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Stress level; Funding: NIH; Summary: Greater alignment with the AHEI-2010 was not associated with risk of GDM.
Bernier, 2023^4^; PCS, Canada, ANGE & PAGG; Analytic N =TM2 FBG=102; TM3 FBG=103; TM2 HOMA-IR=96; TM2 HOMA-IR=98; - Age (y): 32.3±3.5; - Race/Ethnicity (%): White: 97.1; Other: 2.9; - SEP:; ○ Education (%): High school: 4.8; College: 18.3; University: 76.9; ○ Income (%): <40,000 CAD: 4.8; ≥80,000 CAD: 64.4; - Pre-pregnancy BMI (%): 25-29.9: 24.0; 30-34.9: 11.5; 35-39.9: 2.9; ≥40: 2.9 | AHEI-2010 (continuous alignment); 24h recall at: TM1, collected on 2 weekdays and 1 weekend; DP Description:; - Positive components: vegetables, fruit, whole grains, nuts and legumes, long-chain (n-3) fats, PUFA; - Negative components: SSB and fruit juices, red/processed meat, trans fats, sodium; - Alcohol component excluded; Outcome and assessment methods:; FBG and insulin resistance assessed at: ~21-26 GW, and ~32-38 GW; Blood samples drawn after 12h fast. Insulin resistance calculated using HOMA-IR. | FBG; Nonparametric correlation analysis Spearman correlation coefficient (r); TM2: 0.09, p≥0.05; TM3: 0.02, p≥0.05; HOMA-IR; Nonparametric correlation analysis Spearman correlation coefficient (r); TM2: 0.04, p≥0.05; TM3: −0.11, p≥0.05 | Key confounders accounted for:; Pre-pregnancy BMI; Funding: ANGE: Danone Institute of Canada; Universite Laval PAGG: Universite Laval; Summary: Alignment with the AHEI-2010 was not associated with fasting blood glucose or insulin resistance in the second or third trimester.
Ding, 2021^6^; PCS, China, Tongji MCHC; Analytic N =1,489; - Age (y): Q1: 28.3±3.5; Q4 28.6±3.5; - SEP:; ○ Education (%): ≤9y: Q1: 4.2; Q4: 1.4; ≥16y: Q1: 50.6; Q4: 67.7, p<0.01; ○ Household income (%): ≤1000 Yuan/mo: Q1: 1.2; Q4: 0.2; ≥10,000 Yuan/mo: Q1: 12.7; Q4: 22.8, p<0.01; - Pre-pregnancy BMI: Q1: 21.1±2.9; Q4: 20.7±2.5 | CDGCI-PW (continuous alignment); FFQ at: 16-20 GW; DP Description:; - Positive components: staple foods (cereals and their products, potatoes, and beans other than soybeans); green leafy and colored vegetables (red and yellow); milk and its products (milk, yogurt, formula milk powder); soybean and its products; nuts; lean meat (livestock and poultry meat); animal blood and liver; iodized table salt, iodine-rich seafood; - Negative components: pickled food, fried food, cream cake, chocolate, other high-salt, high-oil, and high-sugar food; Outcome and assessment methods:; Gestational diabetes assessed at: 24-28 GW; Diagnosed following 75 g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/L | GDM; Multivariable logistic regression; OR (95% CI) per 10 pt score increase; 0.38 (0.31, 0.48), p<0.01; Alternately excluding one component of the CDGCI-PW score did not substantively change the association | Key confounders accounted for:; Age, SEP, Pre-pregnancy BMI, Parity,; Other covariates: GWG in TM2; Funding: National Program on Basic Research Project of China; The Fundamental Research Funds for the Central Universities Summary: Greater alignment with the CDGCI-PW was associated with lower risk of GDM.
Flor-Alemany, 2021^8^; PCS, Spain, GESTAFIT; Analytic N =107; - Age (y): 33.2±4.4; - SEP:; ○ Education (%): Low: 10.9; High: 58.8; - Pre-pregnancy BMI (%): 25-29.9: 25.2; ≥30: 10.1; - Smoking (%): Current: 8.4; Former: 37.0 | MedDietScore (continuous alignment); FFQ at: 16 GW; DP Description:; - Positive components: Vegetables; Potatoes; Legumes; Fruits; Whole Grains; Fish; Olive Oil; - Negative components: Red and Processed Meat; Poultry; Full-Fat Dairy; - Alcohol component excluded; Outcome and assessment methods:; FBG assessed at: 34 GW; Blood drawn after overnight fast | FBG; Linear regression; β, mg/dL; −0.171, p=0.079 | Key confounders accounted for:; Age, Physical activity, SEP, Pre-pregnancy BMI, Smoking; Funding: Regional Ministry of Health of the Junta de Andalucía; University of Granada, Unit of Excellence on Exercise and Health (UCEES); Spanish Ministry of Education, Culture and Sports; Summary: Alignment with the MedDietScore at 16 GW was not associated with fasting blood glucose at 34 GW.
Flor-Alemany, 2022^9^; PCS, Spain, GESTAFIT; Analytic N =107; - Age (y): 32.9±4.6; - SEP:; ○ Education (%): University: 59.2; ○ Employment (%): 68.4; - Pre-pregnancy BMI: 24.2±4.2; - Smoking (%): Current: 8.6; Former: 38.2 | MedDietScore (continuous alignment); FFQ at: 16 GW; DP Description:; - Positive components: Vegetables; Potatoes; Legumes; Fruit; Whole Grains; Fish; Olive Oil; - Negative components: Red and Processed Meat; Poultry; Full-Fat Dairy; - Alcohol component excluded; Outcome and assessment methods:; Insulin resistance assessed at: 34 GW; Blood samples drawn after fast. HOMA-IR used to calculate insulin resistance. | HOMA-IR; Hierarchical linear regression; β (95% CI); −0.097 (−0.287, 0.092), p=0.312 | Key confounders accounted for:; Physical activity, SEP, Pre-pregnancy BMI; Other covariates: GWG at 34 GW; Funding: Regional Ministry of Health of the Junta de Andalucía; Research and Knowledge Transfer Fund (PPIT) 2016; Excellence Actions Programme: Scientific Units of Excellence (UCEES); Regional Ministry of Economy, Knowledge, Enterprises and University, European Regional Development Funds of the University of Granada; Spanish Ministry of Education, Culture, and Sports; Summary: Alignment with the MedDietScore at 16 GW was not associated with insulin resistance at 34 GW.
Fulay, 2018^11^; PCS, United States, Project Viva; Analytic N =1,701; - Age (y): 32.2±4.9; - Race/Ethnicity (%): White: 71.9; Black: 12.3; Hispanic: 6.5; Asian: 5.6; Other: 3.6; - SEP:; ○ Household income (%): <$20,000/y: 3.1; >$70,000/y: 60.1; ○ Education (%): Primary: 9.4; ≥College: 32.0; - Pre-pregnancy BMI (%): 25-29.9: 21.7; ≥30: 12.9; - Smoking (%): 10.9 | DASH & DASH OMNI (continuous alignment); FFQ at: ~11 GW; DP Descriptions:; [underlined: DASH]; - Positive components: fruit (including fruit juice); vegetables (not potatoes); whole grains; nuts/legumes; low-fat dairy; - Negative components: sodium; SSB; red and/or processed meats; [underlined: DASH OMNI]; - Positive components: fruit (including fruit juice); vegetables (not potatoes); whole grains; nuts/legumes; low-fat dairy; MUFA and PUFA; - Negative components: sodium; SSB; red and/or processed meats; Outcome and assessment methods:; GDM assessed at: 26-28 GW; Diagnosed following 100g OGTT (≥2): fasting ≥95, 1h ≥180, 2h ≥155, 3h ≥140 mg/dL | GDM; Logistic regression; OR (95% CI); [underlined: DASH:] 1.01 (0.96, 1.06); [underlined: DASH OMNI:] 1.01 (0.96, 1.06); Additionally adjusting for Western DP and Prudent DP did not substantively alter the results | Key confounders accounted for:; Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity; Other covariates: GWG until FFQ; TEI; HDP; Funding: NIH; Summary: Greater alignment with DASH or DASH OMNI was not associated with risk of GDM.
Hillesund, 2018^15^; PCS, Norway, NFFD; Analytic N =578; - Age (y): 28.0±4.4 (%): ≥35: 6.8; - Race/Ethnicity (%): “Predominantly White”; - SEP:; ○ Education (%): ≤12y: 31.8; ≥16y: 35.5; ○ Occupation (%): Work outside home: 84.2; Student: 8.7; Unemployed: 3.9; Sick leave/disabled: 1.9; Homemaker: 1.4; ○ Income (%): ≤400,000 NOK: 31.2; >700,000 NOK: 34.4; NR: 6.6; - Pre-pregnancy BMI (%): 25-29.9: 20.2; ≥30: 7.6; - History of GDM (%): 100% nulliparous; - Smoking (%): 3.9 | NFFD diet (continuous alignment); FFQ at: ~15 GW; DP Description:; - Positive components: regular meals; drinking water when thirsty; vegetables w/ dinner; fruits and vegetables btw meals; reading nutrition labels before buying; - Negative components: sweets and snacks without appreciation; large portion sizes of unhealthy foods; added sugar; salt; eating beyond satiety; Outcome and assessment methods:; GDM assessed at: 30 GW; Obtained from hospital charts.; Diagnosed following 75g OGTT: 2 h ≥7.8 mmol/L. | GDM; Multivariate logistic regression; OR (95% CI) per 1 pt score increase; 1.00 (0.86, 1.15), p=0.949; Sensitivity analysis confined to the control group in the original trial did not materially impact the results | Key confounders accounted for:; Age, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Marital status; Randomization assignment
Hillesund, 2018^15^ cont.; Analytic N =468 | | GDM; Multivariate logistic regression; OR (95% CI); 0.98 (0.83, 1.16), p=0.810; Sensitivity analysis confined to the control group in the original trial did not materially impact the results | Key confounders accounted for:; Age, Physical activity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Marital status; Randomization assignment; Funding: South-Eastern Norway Regional Health Authority; Municipalities of southern Norway; University of Agder; Summary: The Norwegian Fit for Delivery diet score in early pregnancy was not significantly associated with GDM, both with and without controlling for physical activity.
Hrolfsdottir, 2019^16^; PCS, Iceland, PREWICE; Analytic N =1,651; - Age (y): 30.3±5.2; - SEP:; ○ Education (%): Elementary: 13; University: 35; Higher academic: 24; - Pre-pregnancy BMI: (%): 25–29.99: 24; ≥30: 19; - Smoking (%): 6.0 | Dietary risk score (categorical alignment, continuous alignment); FFQ at: 11-14 GW; DP Description:; - Positive components: Non-varied diet; SSB/artificially sweetened beverages; Sweets, ice cream, cakes, cookies; Processed meat; - Negative components: Whole grain products; Dairy; Vitamin D; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 75g OGTT: fasting ≥93, 1h ≥180, or 2h ≥153 mg/dL | GDM; Logistic regression; RR (95% CI); [underlined: Categorical]; 3 vs. ≤2 (Ref): 0.96 (0.72, 1.30), p≥0.05; 4 vs. ≤2 (Ref): 1.00 (0.74, 1.37), p≥0.05; ≤5 vs. ≤2 (Ref): 1.38 (1.03, 1.85), p<0.05; p for trend=0.02; [underlined: Continuous]; All participants: 1.10 (1.02, 1.20), p<0.05; BMI <25: 1.11 (0.90, 1.36), p≥0.05; BMI ≥25: 1.09 (1.002, 1.19), p<0.05 | Key confounders accounted for:; Age, SEP, Pre-pregnancy BMI, Smoking, Parity; Other covariates: Family history of T2 DM; Funding: University of Iceland; The Technology Development Fund; RANNIS; Summary: Greater alignment with a dietary risk score was associated with higher risk of GDM among all participants and participants with pre-pregnancy BMI ≥25. Alignment with a dietary risk score was not associated with risk of GDM among participants with pre-pregnancy BMI<25.
Karamanos, 2014^18^; PCS, Algeria, France, Greece, Italy, Lebanon, Malta, Morocco^*^, Serbia, Syria^*^, Tunisia, GRMRS; * Classified as medium or low on the Human Development Index; Analytic N =1,003; - Age (y): No GDM (ADA): 29.9; GDM: 31.9; - Pre-pregnancy BMI: No GDM (ADA): 24.4; GDM: 26.7; - History of GDM: Included, prevalence NR | MDI (tertile 3 vs. tertile 1); FFQ at: NR; DP Description:; - Positive components: bread, cereals, legumes, vegetables, fruits, fish, olive oil:animal fat, potatoes,; - Negative components: meat, eggs, cheese, dairy products; Outcome and assessment methods:; GDM at: 24-32 GW; Diagnosed following 75g OGTT:; ADA (≥2): fasting ≥5.3, 1h ≥10.0, 2h ≥8.6 mmol/l; IADPSG: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/l | GDM; Logistic regression with Bonferroni-adjustment; OR (95% CI); [underlined: ADA criteria]; 0.618 (0.401, 0.95), p=0.030; [underlined: IADPSG criteria]; 0.655 (0.495, 0.867), p=0.004 | Key confounders accounted for:; Age, Pre-pregnancy BMI; Other covariates: Family history of DM, TEI, GWG; Funding: Mediterranean Group for the Study of Diabetes; Summary: Greater alignment with the MDI was associated with a lower risk of GDM.
Li, 2021^19^; PCS, United States, NICHD Fetal Growth Studies– Singletons; Analytic N =8-13 GW: 1,483; 16-22 GW: 1,648; - Age (y):; ○ AHEI: Q1: 25.9±5.57; Q4: 30.5±4.84, p<0.001; ○ aMED: Q1: 26.4±5.70; Q4: 29.9±5.29, p<0.001; ○ DASH: Q1: 25.5±5.43; Q4: 30.4±4.84, p<0.001; - Race/Ethnicity (%):; ○ AHEI: NHB: Q1: 49.1; Q4: 14.9; Hispanic: Q1: 24.1; Q4: 26.2; NHW: Q1: 17.9; Q4: 27.5; AAPI: Q1: 8.9; Q4: 31.4, p<0.001; ○ aMED: NHB: Q1: 39.9; Q4: 22.4; Hispanic: Q1: 28.7; Q4: 25.4; NHW: Q1: 20.5; Q4: 26.0; AAPI: Q1: 11.0; Q4: 26.3, p<0.001; ○ DASH: NHB: Q1: 55.3; Q4: 14.0; Hispanic: Q1: 21.5; Q4: 29.2; NHW: Q1: 10.1; Q4: 37.5; AAPI: Q1: 13.1; Q4: 19.3, p<0.001; - Education (%):; ○ AHEI: <High school: Q1: 12.2; Q4: 9.4; High school/equivalent: Q1: 27.5; Q4: 12.4; Graduate degree: Q1: 6.9; Q4: 28.7, p<0.001; ○ aMED: <High school: Q1: 14.6; Q4: 8.3; High school/equivalent: Q1: 27.8; Q4: 12.4; Graduate degree: Q1: 9.0; Q4: 26.0, p<0.001; ○ DASH: <High school: Q1: 14.8; Q4: 8.5; High school/equivalent: Q1: 31.0; Q4: 10.5; Graduate degree: Q1: 5.6; Q4: 30.6, p<0.001; - Pre-pregnancy BMI (%):; ○ AHEI: 25-29: Q1: 29.8; Q4: 21.3; ≥30: Q1: 20.3; Q4: 11.4, p<0.001; ○ aMED: 25-29: Q1: 30.1; Q4: 22.4; ≥30: Q1: 21.3; Q4: 9.7, p<0.001; ○ DASH: 25-29: Q1: 29.6; Q4: 25.1; ≥30: Q1: 19.0; Q4: 11.6, p=0.01; - History of GDM (%): Pre-pregnancy BMI <30: 0.0; - Smoking (%): Pre-pregnancy BMI <30: 0.0 | AHEI-2010, aMED, & DASH (quartiles of alignment); FFQ at: 8-13 GW; 24h recall at 16-22 GW, 24-29 GW; DP Descriptions:; [underlined: AHEI-2010]; - Positive components: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA; - Negative components: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Sodium; - Alcohol and trans-fat components excluded; [underlined: aMED]; - Positive components: Vegetables; Fruit; Nuts; Fish; Lean Meat (poultry, lean beef); - Negative components: Red and Processed Meat; Sodium.; - Neutral components: Grains and Starches; Dairy Foods; - Alcohol component excluded; [underlined: DASH]; - Positive components: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; - Negative components: Red and Processed Meat; Sweetened Beverages; Sodium; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Extracted from medical records.; Defined as receipt of GDM medications and/or 100g OGTT (≥2): fasting ≥95, 1h ≥180, 2h ≥155, 3h ≥140 mg/dL | GDM; Log-binomial regression; RR (95% CI); [underlined: AHEI-2010]; 8-13 GW; Q2 vs. Q1 (Ref): 0.49 (0.26, 0.92), p<0.05; Q3 vs. Q1 (Ref): 0.51 (0.28, 0.95), p<0.05; Q4 vs. Q1 (Ref): 0.60 (0.31, 1.16), p≥0.05; p for trend=0.17; 16-22 GW; Q2 vs. Q1 (Ref): 0.69 (0.40, 1.20), p≥0.05; Q3 vs. Q1 (Ref): 0.68 (0.38, 1.21), p≥0.05; Q4 vs. Q1 (Ref): 0.32 (0.16, 0.66), p<0.05; p for trend=0.002; [underlined: aMED]; 8-13 GW; Q2 vs. Q1 (Ref): 1.14 (0.60, 2.14), p≥0.05; Q3 vs. Q1 (Ref): 1.00 (0.46, 2.15), p≥0.05; Q4 vs. Q1 (Ref): 0.61 (0.25, 1.48), p≥0.05; p for trend=0.33; [underlined: DASH]; 8-13 GW; Q2 vs. Q1 (Ref): 1.04 (0.55, 1.97), p≥0.05; Q3 vs. Q1 (Ref): 1.01 (0.52, 1.96), p≥0.05; Q4 vs. Q1 (Ref): 0.71 (0.32, 1.56), p≥0.05; p for trend=0.42 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Marital status; family history of DM; Sleep duration; TEI; Funding: NICHD; AARA; Summary: Moderate, but not high, alignment with the AHEI-2010 at 8-13 GW was associated with reduced risk of GDM versus low alignment, while greater alignment with the AHEI-2010 at 16-22 GW was associated with reduced risk of GDM. All associations with aMED and DASH at 8-13 GW were non-significant.
Lindsay, 2020^20^; PCS, United States, UC Irvine; Analytic N =TM1: 184; TM2: 197s; - Age (y): 27.95±5.30; - Race/Ethnicity (%): Non-Hispanic: 52.7; Hispanic: 42.9; - SEP:; ○ SES Index: 3.23±0.93; - Pre-pregnancy BMI: 25.0–29.9: 25.1; ≥30: 21.2; - Smoking (%): 7.4 | MDS (continuous alignment); 24h recall at: TM1 (12.9±1.7 GW) and TM2 (20.5±1.4 GW); DP Description:; - Positive components: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA:SFA; - Negative components: Red and Processed Meat; Dairy Products; - Alcohol component excluded; Outcome and assessment methods:; Insulin resistance assessed at: TM3; Blood samples collected after fast. HOMA-IR used to calculate insulin resistance. | HOMA-IR; Linear regression; β±SE (95% CI); [underlined: TM1 MDS]; −0.059±0.037 (−0.133, 0.015), p=0.118; [underlined: TM2 MDS]; 0.006±0.034 (−0.062, 0.073), p=0.867 | Key confounders accounted for:; Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity; Other covariates: Negative affect; Funding: NIH; Summary: Alignment with the MDS in early and mid-pregnancy was not associated with third trimester insulin resistance.
Lindsay, 2022^21^; PCS, United States, nuMoM2b; Analytic N=GDM: 7,997; 50g non-fasting OGTT: 6,845; 75g OGTT: 569; 100g OGTT: 1,116; - Age (y): Q1: 23.7±5.1; Q4: 30.6±4.3, p<0.001; - Race/Ethnicity (%): NHW: Q1: 48.4; Q4: 76.8; Hispanic: Q1: 20.0; Q4: 9.5; NHB: Q1: 24.0; Q4: 2.8; Other: Q1: 6.6; Q4: 4.1; Asian: Q1: 1.0; Q4: 6.8, p<0.001; - SEP:; ○ Education (%): ≤High school: Q1: 39.2; Q4: 2.0;; Postgraduate: Q1: 5.8; Q4: 46.5, p<0.001; ○ Below federal poverty threshold (%): Q1: 34.2; Q4: 3.3, p<0.001; - Early pregnancy BMI (%): 25-29.9: Q1: 23.3; Q4: 23.7; 30-34.9: Q1: 13.6; Q4: 7.9; ≥35: Q1: 14.9; Q4: 4.8, p<0.001; - History of GDM (%): 100% nulliparous; - Smoking (%): Before pregnancy: Q1: 30.2; Q4: 6.6, p<0.001 | AHEI-2010 (continuous alignment, quartiles of alignment); FFQ at: 6-<14 GW; DP Description:; - Positive components: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA.; - Negative components: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium.; - Moderate component: Alcohol; Outcome and assessment methods:; 75g OGTT assessed at: 26±3 GW; 100g OGTT assessed at: 28±3 GW; Multiple OGTT: time point closest to 26-28 GW; Elevated BG: 1h ≥140 mg/dL in 50g non-fasting OGTT. GDM abstracted from medical records based on local diagnostic criteria:; 75g OGTT: fasting ≥92, 1h ≥180, or 2h ≥153 mg/dL 100g OGTT (≥2): fasting ≥95, 1h ≥180, 2h ≥155, 3h ≥140 mg/dL | GDM; Logistic regression; β, OR (95% CI); [underlined: All participants]; −0.014, 0.986 (0.974, 0.998), p=0.023; [underlined: Using 75g OGTT]; −0.015, 0.985 (0.946, 1.026), p=0.473; [underlined: Using 100g OGTT]; −0.018, 0.983 (0.967, 0.998), p=0.029; Elevated BG; Logistic regression; β, OR (95% CI); −0.006, 0.996 (0.986, 1.001), p=0.092; 50g non-fasting OGTT; Linear regression; β±SE (95% CI), mg/dL; [underlined: 1h BG]; −0.108±0.034 (−0.174, −0.041), p=0.034; 75g OGTT; Linear regression; β±SE (95% CI), mg/dL; [underlined: FBG]; −0.072±0.050 (−0.170, 0.026), p=0.147; [underlined: 1h BG]; −0.374±0.153 (−0.675, −0.073), p=0.015; [underlined: 2h BG]; −0.354±0.137 (−0.625, −0.084), p=0.010; 100g OGTT; Linear regression; β±SE (95% CI), mg/dL; [underlined: FBG]; −0.062±0.034 (−0.130, 0.005), p=0.069; [underlined: 1h BG]; −0.247±0.090 (−0.424, −0.071), p=0.006; [underlined: 2h BG]; −0.243±0.090 (−0.420, −0.065), p=0.007; [underlined: 3h BG]; −0.228±0.087 (−0.400, −0.056), p=0.009 | Key confounders accounted for:; Age, Race/ethnicity, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: GWGR; TEI; NVP; Study site; Funding: NICHD; Clinical and Translational Science Institutes of Indiana University and UC Irvine; Summary: Greater alignment with the AHEI-2010 was associated with reduced risk of GDM in all participants and participants who were diagnosed using a 100g OGTT, but not among participants who were diagnosed using a 75g OGTT. Greater alignment with the AHEI-2010 was also associated with lower post-glucose load BG for all OGTT and all time points. Alignment with the AHEI-2010 was not associated with risk of elevated BG in the 50g non-fasting OGTT or with FBG in the 75g and 100g OGTT, although the association neared significance for the 100g OGTT.
Makarem, 2022^23^; PCS, United States, nuMoM2b; Analytic N =7,798; - Age (y): 27.4±5.5 (%): ≥35: 9.7; - Race/Ethnicity (%): NHW: 63.9; Hispanic: 16.6; NHB: 10.5; Asian: 4.3; Other: 4.6; - SEP:; ○ Education (%): <High school: 5.7; ≥Bachelor’s: 55.6; - Baseline BMI ≥30 (%): 19.5; - History of GDM (%): 100% nulliparous; - Smoking (%): Ever: 41.4 | aMed (categorical alignment, quintiles of alignment); FFQ at: 6-<14 GW; DP Description:; - Positive components: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA:SFA; - Moderate component: Alcohol; - Negative component: Red and Processed Meat; - Low: 0-3 score; Moderate: 4-5; High: 6-9; Outcome and assessment methods:; GDM assessed at: NR; All outcomes were adjudicated by a panel of maternalfetal medicine experts. | GDM; Multivariable logistic regression; OR (95% CI); [underlined: Categorical]; Moderate vs. Low (Ref): 0.88 (0.64, 1.20), p=0.41; High vs. Low (Ref): 0.63 (0.44, 0.90), p=0.01; [underlined: Quintiles]; 2 vs. 1 (Ref): 0.72 (0.51, 1.02), p=0.06; 3 vs. 1 (Ref): 0.73 (0.48, 1.12), p=0.15; 4 vs. 1 (Ref): 0.61 (0.38, 0.95), p=0.03; 5 vs. 1 (Ref): 0.46 (0.28, 0.75), p=0.002 p for trend=0.07 | Key confounders accounted for:; Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Marital status; Family history of CVD; Funding: NIH/ORWH BIRCWH; NIH/NHLBI; NIH/NICHD; OBSSR; NCATS; NIH/NIA; the Barbra Streisand Women’s Cardiovascular Research and Education Program; the Erika J. GlazerWomen’s Heart Research Initiative; AHA; NIH/NINDS; the Gerstner Family Foundation; Summary: Greater alignment with aMed was associated with reduced risk of GDM.
Meinila, 2017^24^; PCS, Finland, RADIEL (control arm); Analytic N =137; - Age (y): Low: 31±4; High: 33±4; - SEP:; ○ Education (y): Low: 13±2; High: 15±2, p=0.009; - Baseline BMI: Low: 31±5; High: 31±7; - History of GDM (%): Low: 42; High: 55; Nulliparous (%): Low: 42: High: 24 | HFII (continuous alignment, categorical alignment); FFQ at: TM1; DP Description:; - Positive components: Vegetables; fruits and berries; fish; high-fiber grains; vegetable oils as cooking fat; oil-based fat spreads; - Negative components: Snacks; SSB; fast food; - Low: 0-7 score; Moderate: 8-12; High: 13-17; Outcome and assessment methods:; GDM, OGTT assessed at: 24-28 GW; GDM diagnosed following 75g OGTT: fasting ≥5.3 mmol/L, 1 h ≥10.0 mmol/L, or 2 h ≥8.6 mmol/L | GDM; Logistic regression; OR (95% CI); Continuous: 0.91 (0.78, 1.07); Middle vs. Low (Ref): 0.64 (0.21, 1.96); High vs. Low (Ref): 0.29 (0.07, 1.28); p for trend=0.09; OGTT; Linear regression with linear contrast; β (95% CI), mmol/L; [underlined: FBG]; Continuous: −0.02 (−0.04, −0.002); Middle vs. Low (Ref): 0.02 (−0.11, 0.15); High vs. Low (Ref): −0.14 (−0.31, 0.01); p for trend=0.053; [underlined: 1h BG]; Continuous: 0.02 (−0.07, 0.12); Middle vs. Low (Ref): 0.07 (−0.63, 0.77); High vs. Low (Ref): −0.27 (−1.18, 0.58); p for trend=0.5; [underlined: 2h BG]; Continuous: −0.09 (−0.18, −0.002); Middle vs. Low (Ref): −0.26 (−0.9, 0.38); High vs. Low (Ref): −0.91 (−1.68, −0.13); p for trend=0.019 | Key confounders accounted for:; Age, Physical activity, SEP, Pre-pregnancy BMI, History of GDM; Funding: Ahokas Foundation; Finnish Foundation for Cardiovascular Disease; Special State Subsidy for Health Science Research of Helsinki University Central Hospital; Samfundet Folkhälsan; The Finnish Diabetes Research Foundation; Foundation for Medical Research Liv och Hälsa; Kulturfonden; Juho Vainio Foundation; State Provincial Office of Southern Finland; The Social Insurance Institution of Finland.; Summary: Among participants at high risk for GDM, greater alignment with HFII trended toward a lower risk of GDM, but did not reach statistical significance. Greater alignment with HFII was significantly inversely associated with fasting glucose and 2h blood glucose post 75g OGTT. Alignment with HFII was not associated with 1h blood glucose post 75g OGTT
Rifas-Shiman, 2009^29^; PCS, United States, Project Viva; Analytic N =1,777; - Age (y): 32.4±4.9; - Race/Ethnicity (%): White: 72; Other, ≥1 race: 16; Black/African American: 12; - SEP:; ○ Education (%): ≤High school diploma: 9; College graduate: 69; ○ Household income <$40K (%): 13; - Pre-pregnancy BMI (%): 25-29.9: 21; ≥30: 14 | AHEI-P (continuous alignment); FFQ at 11.7±3.1 GW; DP Description:; - Positive components: vegetables, fruit, white meat (poultry or fish):red meat, fiber, PUFA:SFA, and folate, calcium, and iron from foods; - Negative component: trans fat; Outcome and assessment methods:; GDM and impaired glucose tolerance at: 26-28 GW; GDM diagnosed following failed non-fasting, 50g OGTT (1h ≥140 mg/dL) and 100g OGTT (≥2): fasting ≥95 mg/dL, 1h ≥180, 2h ≥155, 3h ≥140 mg/dL Impaired glucose tolerance diagnosed following failed non-fasting, 50g OGTT and ≤1 abnormal result on 100g OGTT | GDM; Multinomial Logistic Regression; OR (95% CI) per 5 pt score increase; 0.97 (0.87, 1.08); Impaired Glucose Tolerance; Multinomial Logistic Regression; OR (95% CI); Impaired vs normal (ref) glucose tolerance: 1.00 (0.93, 1.08) | Key confounders accounted for:; Age, Race/ethnicity, SEP, Parity, Pre-pregnancy BMI; Funding: NIH; Harvard Medical School; Harvard Pilgrim Health Care Foundation; Summary: Greater alignment with the AHEI-P was not associated with risk of GDM or impaired glucose tolerance.
Ruiz-Gracia, 2016^45^; RCS, Spain, St. Carlos Hospital; Analytic N= None: 25; Four: <611; - Age (y): (%): ≥35y: 34.9; - Pre-pregnancy BMI: (%): 25-29.9: 20.6; ≥30: 7.4; - History of GDM (%): No prior miscarriage, GDM or gestational HTN: 70.5 | Nutrition variables at risk (None vs. Four); FFQ at: 1st prenatal visit and 24-28 GW; DP Description:; - Positive components: Nuts; - Negative components: High glucose-load refined cereals; Juices and/or sweetened drinks; Biscuit and pastries; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 75g OGTT: fasting ≥92, 1h ≥180, or 2h ≥153 mg/dL | GDM; Binary logistic regression; OR (95% CI); [underlined: Pre-pregnancy BMI <25] 0.29 (0.06, 1.41), p=0.127; [underlined: Pre-pregnancy BMI ≥25] 0.11 (0.01, 0.93), p=0.043; p-for-interaction=0.498 | Key confounders accounted for:; Pre-pregnancy BMI
Ruiz-Gracia, 2016^45^ cont. | | GDM; Binary logistic regression; OR (95% CI); [underlined: Age <35y]; 0.20 (0.06, 0.74), p=0.016; [underlined: Age ≥35y]; 0.34 (0.03, 3.41), p=0.360; p-for-interaction=0.732 | Key confounders accounted for:; Age
Ruiz-Gracia, 2016^45^ cont. | | GDM; Binary logistic regression; OR (95% CI); [underlined: Primiparous]; 0.22 (0.06, 0.81), p=0.023; [underlined: Multiparous]; 0.17 (0.02, 1.49), p=0.110; p-for-interaction=0.463 | Key confounders accounted for:; Parity; Funding: Fundacion para Estudios Endocrinometabolicos; IdISSC Hospital Clinico San Carlos; the Instituto de Salud Carlos III of Spain; Summary: Having no nutrition risk factors compared to 4 nutrition risk factors was associated with reduced risk of GDM in participants with Pre-pregnancy BMI ≥25, <35y, and who were primiparous. Having no nutrition risk factors compared to 4 nutrition risk factors was not associated with risk of GDM in participants with pre-pregnancy BMI <25, ≥35y, or who were multiparous.
Sauder, 2016^30^; PCS, United States, The Healthy Start Study; Analytic N =832; - Age (y): Normal: 28.0±6.1; Dysglycaemia: 29.5±5.8, p=0.01; - Race/Ethnicity (%): NHW: Normal: 57; Dysglycaemia: 46; Hispanic: Normal: 24; Dysglycaemia: 33; Black: Normal: 14; Dysglycaemia: 12; Other: Normal: 6; Dysglycaemia: 9, p=0.05; - SEP:; ○ Education (%): <High school: Normal: 13; Dysglycaemia: 15; High school/GED: Normal: 17; Dysglycaemia: 16; Graduate degree: Normal: 23; Dysglycaemia: 24; ○ Employment (%): Full-time student: Normal: 9; Dysglycaemia: 11; Part-time student: Normal: 6; Dysglycaemia: 4; Employed: Normal: 57; Dysglycaemia: 64; ○ Household income (%): <$40,000: Normal: 28; Dysglycaemia: 34; >$70,000: Normal: 19; Dysglycaemia: 13; Missing: Normal: 36; Dysglycaemia: 31; - Pre-pregnancy BMI: Normal: 25.5±6.2; Dysglycaemia: 27.6±7.0, p=0.003; - History of GDM (%): Normal: 1; Dysglycaemia: 7, p=0.0002; - Smoking (%): Normal: 7; Dysglycaemia: 6 | HEI-2005 (≥64 vs. <64 score); 24h recall at: 1-7x prior to 27 GW; DP Description:; - Positive components: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit (including juice); Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils; - Negative components: SFA; Sodium; Calories from solid fats, alcohol, and added sugars; Outcome and assessment methods:; Dysglycaemia assessed at: 24-28 GW; Abstracted from medical records. Dysglycaemia defined as abnormal 50g glucose challenge; abnormal value on 100g OGTT (≥1): fasting ≥95, 1h ≥180, 2h ≥155, 3h ≥140 mg/dL; or clinical GDM diagnosis | Dysglycaemia; Logistic regression; OR (95% CI); 0.71 (0.45, 1.10), p≥0.05; Further adjustment for GWG through 26 GW did not substantively change the results | Key confounders accounted for:; Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Family history of DM; Funding: NIH; Summary: Alignment with the HEI-2005 was not associated with risk of dysglycaemia.
Tranidou, 2023^31^; PCS, Greece, BORN2020; Analytic N =743; - Age (y): 32.1±4.85 (%): >35: 27.9; - Pre-pregnancy BMI: (%): 25-29.9: 20.7; ≥30: 12.3; - Pre-existing DM (%): 0.0; - Smoking (%): 10.0 | MDS & Modified MDS (categorical alignment); FFQ at: 11-<14 GW; DP Descriptions:; [underlined: MDS]; - Positive components: Vegetables; Legumes; Fruit and Nuts; Cereals; Fish; MUFA:SFA; - Negative components: Red and Processed Meat; Dairy Products; - Moderate component: Alcohol; - Low: 0-3 score; Moderate: 4; High: 5-9; [underlined: Modified MDS]; - Positive components: Vegetables (not potatoes); Legumes and nuts; Fruits; Whole grain cereals; Lean meat; Fish and shellfish; Low fat and fermented dairy products; Olive and canola oil; Olives; - Negative components: Fatty meat and processed meat; Full fat dairy products not fermented; Sugar; - Wine component excluded; - Low: 0-3.5 score; Moderate: 4-4.5; High: 5-14; Outcome and assessment methods:; GDM assessed at: 24-38 GW; Diagnosed following 75g OGTT: fasting ≥92, 1h ≥180, or 2h ≥153 mg/dL | GDM; Multiple logistic regression; OR (95% CI); [underlined: MDS]; Moderate vs. Low (Ref): 0.72 (0.40, 1.28), p=0.27; High vs. Low (Ref): 0.57 (0.36, 0.94), p=0.02; [underlined: Modified MDS]; Moderate vs. Low (Ref): 1.02 (0.59, 1.78), p=0.94; High vs. Low (Ref): 0.85 (0.47, 1.55), p=0.59 | Key confounders accounted for:; Age, Physical activity, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Funding: None; Summary: Greater alignment with the MDS was associated with reduced risk of GDM. Alignment with the modified MDS was not associated with risk of GDM.
Tryggvadottir, 2016^32^; PCS, Iceland, Landspitali National University Hospital; Analytic N =168; - Age (y): ~29.5; - Pre-pregnancy BMI (%): 25-29.9: 26; ≥30: 23; - History of GDM (%): 0.0; - Smoking (%): 0.0 | Icelandic HEI (tertiles of alignment); 4-day weighed food record at 19-24 GW; DP Description:; - Positive components: fish and seafood; vegetables; fruits; vegetable oils; nuts and seeds; unground/whole ground cereals; vitamin D; - Negative components: soft drinks; Outcome and assessment methods:; GDM at: 23-28 GW; Diagnosed following 75g OGTT: fasting 5.1-6.9, 1h ≥10.0, or 2h 8.5–11.0 mmol/l | GDM; Chi-squared, N (%); [underlined: Pre-pregnancy BMI >25] (N=82); T1/T2: 14 (25.0); T3: 1 (3.8); p=0.02 | Key confounders accounted for:; Pre-pregnancy BMI; Funding: University of Iceland, Landspitali National University Hospital; Summary: Greater alignment with the Icelandic HEI was associated with a lower GDM diagnosis rate among participants with pre-pregnancy BMI ≥25.
Wang, 2021^33^; PCS, China, Tongji MCHC; Analytic N =2,099; - Age (y): Median (IQR): 28.0 (26.0, 30.0); - Race/Ethnicity (%): Han ethnicity: 97.7; - SEP:; ○ Education (%): ≤12y: 13.9; ≥16y: 59.3; ○ Average income (%): <5000 CNY/mo: 37.5; ≥10000 CNY/mo: 18.4; - Pre-pregnancy BMI: Median (IQR): 20.4 (18.8, 22.2); - History of GDM (%): 0.0; - Smoking (%): Pre-pregnancy: 12.7 | PDI, hPDI, & uPDI (continuous alignment, quartiles of alignment); FFQ at: 13-28 GW; DP Descriptions:; [underlined: PDI:]; - Positive components: plant food groups (whole grains, refined grains, fruits, vegetables, nuts, beans, vegetable oil, sweets and desserts); - Negative components: animal food groups (dairy products, eggs, meat and fish); [underlined: hPDI:]; - Positive components: healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); - Negative components: less healthy plant-based foods (fruit juices, refined grains, potatoes, SSB, sweets/desserts); animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods); [underlined: uPDI:]; - Positive components: less healthy plant-based foods (fruit juices, refined grains, potatoes, SSB, sweets/desserts); - Negative components: healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods); Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 75 g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/L | GDM; Logistic regression; OR (95% CI); [underlined: PDI]; Per IQR (6 pt): 0.71 (0.56, 0.90), p<0.05; Q2 vs Q1 (Ref): 0.86 (0.55, 1.35), p≥0.05; Q3 vs Q1 (Ref): 0.76 (0.47, 1.23), p≥0.05; Q4 vs Q1 (Ref): 0.43 (0.24, 0.75), p<0.05; p for trend=0.004; Estimates did not substantively change with the exclusion of each one of twelve food groups from PDI one by one at a time. Estimate remained similar after excluding less healthy plant food groups (refined grains, sweets, and desserts).; [underlined: hPDI]; Per IQR (6 pt): 0.76 (0.60, 0.97), p<0.05; Q2 vs Q1 (Ref): 0.82 (0.51, 1.30), p≥0.05; Q3 vs Q1 (Ref): 0.87 (0.55, 1.39), p≥0.05; Q4 vs Q1 (Ref): 0.55 (0.32, 0.94), p<0.05; p for trend=0.047; [underlined: uPDI]; Per IQR (8 pt): 0.90 (0.69, 1.18), p≥0.05; Q2 vs Q1 (Ref): 0.97 (0.59, 1.60), p≥0.05; Q3 vs Q1 (Ref): 1.12 (0.67, 1.89), p≥0.05; Q4 vs Q1 (Ref): 0.96 (0.54, 1.68), p≥0.05; p for trend=0.947 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Family history of DM; Alcohol intake; Sleep quality; GWG before GDM diagnosis; TEI; Funding: National Program on Basic Research Project of China; Summary: Greater alignment with the PDI was associated with a reduced risk of GDM. Greater alignment with the hPDI was marginally associated with a reduced risk of GDM. Alignment with the uPDI was not associated with risk of GDM.
Yee, 2020^34^; PCS, United States, nuMoM2b; Analytic N =8,259; - Age (y): Q1: 23.9±5.2; Q4: 29.9±4.5, p<0.001; - Race/Ethnicity (%): NHW: Q1: 47.8; Q4: 74.4; NHB: Q1: 24.0; Q4: 2.8; Hispanic: Q1: 20.3; Q4: 11.9; Other: Q1: 6.3; Q4: 4.0; Asian: Q1: 1.5; Q4: 6.9, p<0.001; - SEP:; ○ Public insurance (%): Q1: 50.7; Q4: 8.4, p<0.001; ○ Household income <200% FPL (%): Q1: 55.7; Q4: 12.4, p<0.001; ○ Education (%): ≥Some college: Q1: 82.0; Q4: 98.8, p<0.001; - Pre-pregnancy BMI: Q1: 27.1±7.3; Q4: 24.9±4.9, p<0.001; - History of GDM (%): 100% nulliparous; - Smoking (%): Ever used tobacco: Q1: 50.7; Q4: 36.6, p<0.001 | HEI-2010 (quartiles of alignment); FFQ at: 6-13 GW; DP Description:; - Positive components: Total Vegetables; Greens and Beans; Total Fruit (including juice); Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids; - Negative components: Refined Grains; Empty Calories (i.e., energy from solid fats, alcohol, and added sugars); Sodium; Outcome and assessment methods:; GDM assessed at: NR; Clinical records reviewed using each site’s local protocol for diagnosis. | GDM; Multivariable Poisson Regression; RR (95% CI); Q1 vs. Q4 (Ref): 1.09 (0.78, 1.53), p≥0.05; Q2 vs. Q4 (Ref): 1.07 (0.79, 1.35), p≥0.05; Q3 vs. Q4 (Ref): 1.00 (0.74, 1.35), p≥0.05 | Key confounders accounted for:; Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Chronic HTN, Mental health disorder, Marital status; Funding: NICHD; Clinical and Translational Science Institutes of Indiana University and UC Irvine; Summary: Alignment with the HEI-2010 was not associated with risk of GDM.
Factor/Cluster Analysis
Angali, 2020^1^; PCS, Iran (Islamic Rep. of), Ahvaz Jundishapur University of Medical Sciences; Analytic N =488; - Age (y): HFF: T1: 28.7±5.8; T3: 27.3±5.7; VFP: T1: 27.8±6.4; T3: 28.0±5.4; - Race/Ethnicity (%): Arabian ethnicity: 100; - SEP:; ○ Family income (%): HFF: <$132/mo: T1: 9.4; T3: 45.2; >$368/mo: T1: 44.2; T3: 31.6, p=0.001; VFP: <$132/mo: T1: 42.9; T3: 38.1; >$368/mo: T1: 35.1; T3: 35.1; ○ Education (%): HFF: <12 grade: T1: 28.1; T3: 40.4 >12 grade: T1: 35.7; T3: 30.7; VFP: <12 grade: T1: 41.1; T3: 30.1; >12 grade: T1: 30.9; T3: 33.6; ○ Job (%): HFF: Homemaker: T1: 32.6; T3: 34.4; Employee: T1: 41.9; T3: 25.6; VFP: Homemaker: T1: 34.2; T3: 33.3; Employee: T1: 32.6; T3: 25.6; - Pre-pregnancy BMI (%): HFF: [underlined: >]25: T1: 37.5; T3: 29.7, p=0.013; VFP: >25: T1: 30.6; T3: 34.4, p=0.027; - Pre-GDM (%): 0.0; - Smoking (%): 0.0 | HFF DP & VFP DP (quartiles of alignment); FFQ at: 13-16 GW; DP Description:; - High fat-fast food (HFF) DP: Higher in pasta, vermicelli, broken wheat, high-fat organ meats, salami, sausage, high -fat dairy, and sugary cool drinks; - Vegetable-fruits and protein (VFP) DP: Higher in vegetable oil, fruit body vegetables, seasonal & non seasonal fruits and low-fat dairy and meat (red and white); Outcome and assessment methods:; FBG assessed at: 24-28 GW; FBG quartile cut points of 25, 50, 75 and 99 were 77, 85, 92 and 123 mg/dl, respectively | FBG Q25; Quartile regression model; β±SE (95% CI), mg/dL; [underlined: HFF DP]: 0.05±0.227 (−0.4, 0.5), p=0.8; [underlined: VFP DP]: 0.15±0.32 (−0.47, 0.77), p=0.6; FBG Q50; Quartile regression model; β±SE (95% CI), mg/dL; [underlined: HFF DP]: 0.22±0.21 (−0.186, 0.64), p=0.28; [underlined: VFP DP]: 0.113±0.21 (−0.4, 0.425), p=0.95; FBG Q75; Quartile regression model; β±SE (95% CI), mg/dL; [underlined: HFF DP]: 0.16±0.136 (−0.112, 0.427 ), p=0.25; [underlined: VFP DP]: 0.047±0.15 (−0.249, 0.342), p=0.75; FBG Q99; Quartile regression model; β±SE (95% CI), mg/dL; [underlined: HFF DP]: 2.12±1.03 (0.082, 4.116), p=0.04; [underlined: VFP DP]: −1±0.49 (−1.97, −0.03), p=0.043 | Key confounders accounted for:; Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, History of GDM; Funding: Ahvaz Jundishapur University of Medical Sciences and Social Determinants of Health; Summary: Greater alignment with the HFF DP was marginally associated with higher FBG in Q99 (92-123 mg/dL), while greater alignment with the VFP DP was marginally associated with lower FBG in Q99. Alignment with the HFF DP or VFP was not associated with FBG in Q25 (≤77 mg/dL), Q50 (77-85 mg/dL), or Q75 (85-92 mg/dL).*; *Our interpretation is based on the analyses described in the methods section, which differs from what is reported in the results and discussion sections (authors interpreted the results by DP quartile, not FBG quartile).
de Seymour, 2022^5^; PCS, China, CLIMB; Analytic N=1,261; - Age (y): Median (IQR): 28 (26, 31); - Race/Ethnicity (%): Han ethnicity: 97.9; - SEP:; ○ Tertiary level education (%): 63.1; ○ Household income (%): <7,000 yuan/mo: 19.5; >10,000 yuan/mo: 44.5; - Baseline BMI: Median (IQR): 21.0 (19.4, 22.9); - Previous pregnancy complication resulting in delivery <32 GW (%): 0.0 | FPV DP & PSO DP (continuous alignment); FFQ at: 11-14 GW; DP Descriptions:; - Fish, poultry and vegetables (FPV)-based DP: Higher in fish; poultry; legumes and bean products; green leafy vegetables; root vegetables; other vegetables; seafood; fruits; eggs; organ meats; beverages; bread; dairy; soup; nuts; - Pasta, sweetened beverages, oils and condiments (PSO)-based DP: Higher in pasta; sweetened beverages; oils and condiments; fast food; Outcome and assessment methods:; Gestational diabetes assessed at: 22-28 GW; Diagnosed following the 75g OGTT: fasting ≥5.1, 1h ≥10, or 2h ≥8.5 mmol/l | GDM; Binomial logistic regression; OR (95% CI); [underlined: FPV-based DP]: 1.033 (0.879, 1.214), p=0.689; [underlined: PSO-based DP]: 0.961 (0.815, 1.133), p=0.636 | Key confounders accounted for:; Age, Race/ethnicity, SEP, Pre-pregnancy BMI; Other covariates: Offspring sex, TEI, CLIMB treatment group, Other DP; Funding: Joint Health Research Council New Zealand–National Science Foundation of China; Lottery Health New Zealand; Fonterra Co-operative Group Ltd., New Zealand; New Zealand Ministry for Primary Industries; Summary: Alignment with the FPV-based DP and PSO-based DP was not associated with risk of GDM.
Du, 2017^7^; PCS, China, Maternal and Child Health Care Hospital, Tangshan; Analytic N= GDM: 753; HbA1C: 88; - Age (y): 28.0±3.2; - SEP:; ○ Education (%): <College: 17.5; ≥College: 82.5; - Pre-pregnancy BMI: 24-27.9: 14.7; ≥28: 4.0; - Smoking (%): Partner smokes: 46.2 | Western DP, Traditional DP, Mixed DP, & Prudent DP (quartiles of alignment, Western DP, Traditional DP, & Mixed DP vs. Prudent DP); 24h recall at: 5-15 GW and 24-28 GW; DP Descriptions:; - Western DP: Higher in dairy; baked/fried food; white meat; - Traditional DP: Higher in light-colored vegetables; fine grain; red meat; tubers; - Mixed DP: Higher in edible fungi; shrimp/shellfish; red meat; - Prudent DP: Higher in dark-colored vegetables; deep-sea fish; Outcome and assessment methods:; GDM, HbA1C assessed at: 24-28 GW; Outcomes extracted from medical records.; GDM: Diagnosed following 75g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/l High HbA1C: ≥5.1% | GDM; Multiple logistic regression; OR (95% CI); [underlined: Western DP]; Q2 vs. Q1 (Ref): 1.78 (0.72, 4.43), p=0.21; Q3 vs. Q1 (Ref): 3.29 (1.39, 7.82), p=0.007; Q4 vs. Q1 (Ref): 1.68 (0.66, 4.29), p=0.28; p for trend=0.15; [underlined: Traditional DP]; Q2 vs. Q1 (Ref): 1.29 (0.50, 3.33), p=0.60; Q3 vs. Q1 (Ref): 2.86 (1.19, 6.83), p=0.02; Q4 vs. Q1 (Ref): 2.92 (1.19, 7.17), p=0.02; p for trend=0.005; [underlined: Mixed DP]; Q2 vs. Q1 (Ref): 0.88 (0.41, 1.93), p=0.76; Q3 vs. Q1 (Ref): 1.15 (0.56, 2.38), p=0.70; Q4 vs. Q1 (Ref): 0.70 (0.32, 1.55), p=0.39; p for trend=0.56; [underlined: Prudent DP]; Q2 vs. Q1 (Ref): 0.92 (0.43, 1.96), p=0.82; Q3 vs. Q1 (Ref): 1.42 (0.69, 2.92), p=0.34; Q4 vs. Q1 (Ref): 0.49 (0.20, 1.22), p=0.12; p for trend=0.35; [underlined: Western vs. Prudent DP (Ref)] 4.40 (1.58, 12.22), p=0.004; [underlined: Traditional DP vs. Prudent DP (Ref)] 4.88 (1.79, 13.32), p=0.002; [underlined: Mixed DP vs. Prudent DP (Ref)] 1.61 (0.52, 4.97), p=0.41; High HbA1C; Multiple logistic regression; OR (95% CI); [underlined: Western vs. Prudent DP (Ref)] 12.37 (1.47, 103.91), p=0.013; [underlined: Traditional DP vs. Prudent DP (Ref)] 26.23 (2.54, 270.74), p=0.004; [underlined: Mixed DP vs. Prudent DP (Ref)] 7.06 (0.90, 55.45), p=0.06 | Key confounders accounted for:; Age, Physical activity, SEP, Pre-pregnancy BMI, Smoking, Parity,; Other covariates: Family history of DM; TEI; Funding: China Medical Board; the Key Discipline Construction of Public Health of Shanghai; the National Natural Science Foundation of China; Summary: Using averaged TM1 and TM2 data: Greater alignment with the Western DP and Traditional DP is associated with greater risk of GDM. Greater alignment with the Mixed DP and Prudent DP is not associated with risk of GDM. Alignment with the Western DP and Traditional DP is associated with greater risk of GDM and high HbA1C compared to alignment with the Prudent DP. Alignment with the Mixed DP is not associated with risk of GDM or high HbA1C compared to the Prudent DP, although the association neared statistical significance for HbA1C.
Du, 2017^7^ cont.; Analytic N=830 | DP 1, DP 2, DP 3, & DP 4 (quartiles of alignment); 24h recall at: 5-15 GW; DP Descriptions:; - DP 1: Higher in red meat; light-colored vegetables; fine grain; - DP 2: Higher in dark-colored vegetables; freshwater fish; fine grain; - DP 3: Higher in dairy products; baked/fried food; - DP 4: Higher in white meat; tubers | GDM; Multiple logistic regression; OR (95% CI); [underlined: DP 1]; Q2 vs. Q1 (Ref): 0.86 (0.41, 1.81), p=0.69; Q3 vs. Q1 (Ref): 0.71 (0.31, 1.60), p=0.41; Q4 vs. Q1 (Ref): 1.05 (0.48, 2.32), p=0.91; p for trend=0.99; [underlined: DP 2]; Q2 vs. Q1 (Ref): 1.91 (0.91, 4.03), p=0.09; Q3 vs. Q1 (Ref): 2.55 (0.73, 3.30), p=0.26; Q4 vs. Q1 (Ref): 0.57 (0.22, 1.45), p=0.23; p for trend=0.28; [underlined: DP 3]; Q2 vs. Q1 (Ref): 0.88 (0.42, 1.84), p=0.73; Q3 vs. Q1 (Ref): 0.95 (0.46, 1.96), p=0.89; Q4 vs. Q1 (Ref): 0.73 (0.34, 1.58), p=0.43; p for trend=0.92; [underlined: DP 4]; Q2 vs. Q1 (Ref): 2.22 (1.98, 5.03), p=0.06; Q3 vs. Q1 (Ref): 1.92 (0.85, 4.37), p=0.12; Q4 vs. Q1 (Ref): 1.67 (0.73, 3.81), p=0.22; p for trend=0.35 | Key confounders accounted for:; Age, Physical activity, SEP, Pre-pregnancy BMI, Smoking, Parity; Other covariates: Family history of DM; TEI; Funding: China Medical Board; the Key Discipline Construction of Public Health of Shanghai; the National Natural Science Foundation of China; Summary: Using TM1 data only: Alignment with the four identified DPs was not associated with risk of GDM.
Flynn, 2016^10^; PCS, United Kingdom, UPBEAT; Analytic N =857; - Age (y): 30.5±5.5; - Race/Ethnicity (%): White: 64; Black: 23; Asian: 8; Other: 5; - SEP:; ○ Education (%): None/Secondary: 20; Degree/Higher degree: 40; Vocational qualification: 24; ○ Index of multiple deprivation (%): 1 (least deprived): 4; 5 (most deprived): 43; - Pre-pregnancy BMI: 36.2±4.7; ○ (%): ≥30: 100 | Fruit & Veg DP, African/Caribbean DP, Processed DP, & Snacks DP (quartiles of alignment); FFQ at: 15-<19 GW; DP Descriptions:; - Fruit & Veg DP: High intake of bananas; citrus fruit; dried fruit; fresh fruit; green vegetables; pulses; root vegetables; salad vegetables; tropical fruit; yoghurt; - African/Caribbean DP: High intake of red meat; cassava; white meat; rice including pilau, fried or jollof rice; plantain; fish; - Processed DP: High intake of chocolate; crisps; green vegetables; potatoes; processed meat and meat products; root vegetables; squash and fizzy drinks; sugar free squash and fizzy drinks; chips; - Snacks DP: High intake of biscuits and cookies; cakes and pastries; chocolate; full fat cheese; sweets; Outcome and assessment methods:; GDM assessed at: 27-<29 GW; Diagnosed following 75g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/l | GDM; Multiple logistic regression; OR (95% CI); [underlined: Fruit & Veg DP]; Q2 vs. Q1 (Ref): 1.13 (0.71, 1.81); Q3 vs. Q1 (Ref): 1.18 (0.73, 1.89); Q4 vs. Q1 (Ref): 1.03 (0.64, 1.68); p for trend=0.891; [underlined: African/Caribbean DP]; Q2 vs. Q1 (Ref): 1.26 (0.79, 1.99); Q3 vs. Q1 (Ref): 1.13 (0.70, 1.82); Q4 vs. Q1 (Ref): 2.46 (1.41, 4.31); p for trend=0.010; [underlined: Processed DP]; Q2 vs. Q1 (Ref): 1.71 (1.04, 2.82); Q3 vs. Q1 (Ref): 2.03 (1.23, 3.33); Q4 vs. Q1 (Ref): 2.05 (1.23, 3.41); p for trend=0.022; [underlined: Snacks DP]; Q2 vs. Q1 (Ref): 0.94 (0.57, 1.54); Q3 vs. Q1 (Ref): 1.10 (0.67, 1.81); Q4 vs. Q1 (Ref): 1.24 (0.76, 2.01); p for trend=0.666 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Parity; Other covariates: Treatment allocation; Funding: NIHR UK; Scottish Government Health Directorates; Guys and St. Thomas’ Charity; Tommy’s Charity; the European Union’s Seventh Framework Programme; Summary: Among participants with Pre-pregnancy BMI ≥30, greater alignment with the African/Caribbean DP and Processed DP was associated with higher risk of GDM. Alignment with the Fruit & Veg DP or Snacks DP was not associated with risk of GDM.
Hajianfar, 2018^12^ PCS, Iran (Islamic Rep. of), Isfahan University of Medical Sciences; Analytic N =812; - Age (y): 20-40; - SEP:; ○ Occupation (%): Healthy: Homemaker: Q1: 25.3; Q4: 22.2; Employed: Q1: 21.4; Q4: 38.1; Teacher: Q1: 28.9; Q4: 28.9, p=0.01; Western: p=0.4; Traditional: p=0.3; ○ Education (%): Traditional: Undergraduate: Q1: 21.3; Q4: 23; Graduate: Q1: 28.2; Q4: 26.4, p=0.03; Healthy: p=0.9; Western: p=0.4; ○ SES (%): Western: Low: Q1: 32.8; Q4: 14.1; High: Q1: 24.3; Q4: 28.5, p=0.02; Traditional: Low: Q1: 12.5; Q4: 20.3; High: Q1: 27.2; Q4: 30.3, p<0.001; Healthy: p=0.5; - Pre-pregnancy BMI (%): ≥25: Healthy: Q1: 24.2; Q4: 26.1; Western: Q1: 24.7; Q4: 23.6; Traditional: Q1: 26.1; Q4: 25.6 | Healthy DP, Western DP, & Traditional DP (quartiles of alignment); FFQ at: 8-16 GW; DP Description:; - Healthy DP: Higher intake of green vegetables, leafy vegetables, colored vegetables, fruits, low fat dairy, poultry, bulky vegetables, red meat, citrus, nuts, fish, olive, marinades, sweet fruit, egg, and unsaturated fat; - Western DP: Higher intake of processed meats, fruits, fruits juice, citrus, nuts, fish, desserts and sweets, sugar, saturated fat, sweet fruit (melon, persimmon, date, fig, grapes, raisins, berries that have high glycemic index), potato, legumes, coffee, egg, pizza, high fat dairy, whole grain, and soft drinks; - Traditional DP: Higher intake of refined grains, colored vegetables, olive, sugar, salt, spices, unsaturated fat, garlic, onion, and tea; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 50g OGTT: fasting ≥95 and 1h ≥140 mg/dL | GDM; Logistic regression, p-values from Mantel–Haenszel extension chi-squared test; OR (95% CI); [underlined: Healthy DP]; Q2 vs. Q1 (Ref): 0.61 (0.27, 1.43), p≥0.05; Q3 vs. Q1 (Ref): 0.95 (0.43, 2.12), p≥0.05; Q4 vs. Q1 (Ref): 1.04 (0.46, 2.31), p≥0.05; p=0.6; [underlined: Western DP]; Q2 vs. Q1 (Ref): 0.62 (0.25, 1.52), p≥0.05; Q3 vs. Q1 (Ref): 0.91 (0.42, 1.98), p≥0.05; Q4 vs. Q1 (Ref): 0.52 (0.22, 1.25), p≥0.05; p=0.39; [underlined: Traditional DP]; Q2 vs. Q1 (Ref): 0.8 (0.32, 1.99), p≥0.05; Q3 vs. Q1 (Ref): 1.36 (0.58, 3.14), p≥0.05; Q4 vs. Q1 (Ref): 1.71 (0.75, 3.88), p≥0.05; p=0.28 | Key confounders accounted for:; Age, Physical activity, SEP, Pre-pregnancy BMI; Other covariates: TEI; Funding: NR; Summary: Alignment with the Healthy DP, Western DP, or Traditional DP was not associated with risk of GDM.
He, 2015^13^; PCS, China, BIGCS; Analytic N =3,063; - Age (y): 28.9±3.2; - SEP:; ○ Education (%): ≤Middle school: 10; Undergraduate: 53.4; Postgraduate: 11.9; ○ Income (%): <1500 yuan/mo: 8.2; ≥9001 yuan/mo: 14.0; - Pre-pregnancy BMI (%): ≥24: 8.8 | Vegetable, Protein-rich, Prudent, & Sweet and seafood DPs (tertiles of alignment); FFQ at 24-27 GW; DP Descriptions:; - Vegetable DP: Higher in root vegetables, beans, mushrooms, melon vegetables, seaweed, other legumes, fruits, leafy and cruciferous vegetables, processed vegetables, nuts, cooking oil; - Protein-rich DP: Higher in poultry, red meat, animal organ meat, grains (mainly refined), processed meat, fish, soups, leafy and cruciferous vegetables, eggs; - Prudent DP: Higher in dairy products, nuts, eggs, fish, soups, fruits; infrequent intake of processed meat, sugar-sweetened beverages, processed vegetables; - Sweets and seafood DP: Higher in Cantonese desserts, mollusks and shellfish, sugar-sweetened beverages; Lower in grains (mainly refined), leafy and cruciferous vegetables; Outcome and assessment methods:; GDM assessed at: NR; Diagnosed following 75g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/l | GDM; All Participants; Multivariate Regression; RR (95% CI); [underlined: Vegetable DP]; All participants; T3 vs T1 (Ref): 0.79 (0.64, 0.97); T2 vs T1 (Ref): 1.0 (0.83, 1.21); p for trend=0.036; No family history of DM; T3 vs T1 (Ref): 0.94 (0.74, 1.19); With family history of DM; T3 vs T1 (Ref): 0.49 (0.31, 0.76) p for interaction=0.022; [underlined: Protein-rich DP]; T3 vs T1 (Ref): 0.95 (0.78, 1.16); T2 vs T1 (Ref): 0.99 (0.81, 1.20); p for trend=0.659; [underlined: Prudent DP]; T3 vs T1 (Ref): 1.00 (0.82, 1.22); T2 vs T1 (Ref): 0.96 (0.78, 1.17); p for trend=0.914; [underlined: Sweets and seafood DP]; T3 vs T1 (Ref): 1.23 (1.02, 1.49); T2 vs T1 (Ref): 0.84 (0.68, 1.04); p for trend=0.010 | Key confounders accounted for:; Age, SEP, Parity, Pre-pregnancy BMI; Other covariates: Family history of DM (subgroup analyses); Funding: Guangzhou Science and Technology Bureau; Summary: Greater alignment with the Vegetable DP was associated with a lower risk of GDM among all participants and those with a family history of DM, but not among those with no family history of DM. Greater alignment with the Sweets and seafood DP was associated with a higher risk of GDM. The protein-rich DP and Prudent DP were not associated with GDM.
Hehua, 2021^14^; PCS, China, NEC-Biobank; Analytic N =2,244; - Age (y): Mean (95% CI): GDM: 31.67 (31.34, 32.00); No GDM: 30.35 (30.18, 30.52), p<0.0001; - Race/Ethnicity (%): Han: GDM: 84.87; No GDM: 83.14; - SEP:; ○ Education (%): ≥College: GDM: 52.31; No GDM: 55.71; ○ Household income (%): ≥12,000 yuan: GDM: 32.56; No GDM: 33.48; - Pre-pregnancy BMI: Mean (95% CI): GDM: 23.93 (23.57, 24.29); No GDM: 22.20 (22.02, 22.38), p<0.0001; - History of DM (%): 0.0; - Smoking (%): GDM: 3.78; No GDM: 2.04, p=0.04 | Healthy DP, Sweet foods DP, Animal foods DP, & Traditional DP (quartiles of alignment); FFQ at: 0-13 GW, 14-28 GW, and >28 GW; DP Descriptions:; - Healthy DP: High intake of vegetables, eggs, dairy, whole grains, tubers, legumes and legume products, fruits, fish, and nuts; - Sweet foods DP: High intake of ice cream and candy, cake, fruit and vegetable juices, and sugar-containing beverages; - Animal foods DP: High intake of animal blood, animal organs, preserved eggs, and processed meat products; - Traditional DP: High intake of pickled foods, Chinese sauerkraut, ginger, and garlic; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 75g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/l | GDM; Multiple logistic regression; OR (95% CI); [underlined: Healthy DP]; Q2 vs. Q1 (Ref): 0.88 (0.64, 1.20), p≥0.05; Q3 vs. Q1 (Ref): 0.68 (0.47, 0.98), p<0.05; Q4 vs. Q1 (Ref): 0.94 (0.59, 1.51), p≥0.05; [underlined: Sweet foods DP]; Q2 vs. Q1 (Ref): 1.16 (0.86, 1.57), p≥0.05; Q3 vs. Q1 (Ref): 0.96 (0.69, 1.32), p≥0.05; Q4 vs. Q1 (Ref): 0.86 (0.59, 1.25), p≥0.05; [underlined: Animal foods DP]; Q2 vs. Q1 (Ref): 0.77 (0.56, 1.05), p≥0.05; Q3 vs. Q1 (Ref): 1.13 (0.83, 1.54), p≥0.05; Q4 vs. Q1 (Ref): 0.89 (0.64, 1.24), p≥0.05; [underlined: Traditional DP]; Q2 vs. Q1 (Ref): 0.99 (0.72, 1.34), p.0.05; Q3 vs. Q1 (Ref): 0.89 (0.65, 1.22), p≥0.05; Q4 vs. Q1 (Ref): 1.09 (0.80, 1.49), p≥0.05 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Family history of DM; Alcohol intake; Chronic diseases; TEI; Funding: The National Key R&D Project of China; 345 Talent Project of Shengjing Hospital of China Medical University; Summary: Besides the third quartile of the Healthy DP associated with a reduced risk of GDM compared to the first quartile, alignment with the Healthy DP, Sweet foods DP, Animal foods DP, and Traditional DP was not associated with risk of GDM.
Hu, 2019^17^; PCS, China, BISCS; Analytic N =1,014; - Age (y): (%): <25: 6.0; ≥35: 15.2; - Race/Ethnicity (%): Han: 77.9; Minority: 22.1; - SEP:; ○ Education (%): ≤Middle school: 8.5; High school: 14.5; ≥Graduate: 9.6; ○ Household income (%): <30,000 CNY: 24.8; ≥70,000 CNY: 23.2; - Pre-pregnancy BMI: (%): 23.24.9: 14.9; ≥25: 19.3; - Smoking (%): Before or during pregnancy: 1.8 | Traditional DP-TFD, Sweet Foods DP-TFD, Fried Food-Beans DP-TFD, Whole Grain-Seafood DP-TFD, Fish-Seafood DP-FFQ, Protein-Sweets DP-FFQ, & Traditional DP-FFQ (quartiles of alignment); 3d food diaries (TFD) at: 22±1.2 to 24±1.2 GW; FFQ at: 22±1.2 GW; DP Descriptions:; - Traditional DP-TFD: High intake of tubers; vegetables; fruits; rice; red meat; eggs; nuts; - Sweet foods DP-TFD: High intake of pastries and candies; sweet beverages; shrimps, crabs, and mussels; fruits; red meat; - Fried food-beans DP-TFD: High intake of fried foods; beans and products; and dairy products; low intake of organ meats; - Whole grain-seafood DP-TFD: High intake of whole grains; shrimps, crabs, and mussels; nuts; and seaweed; low intake of eggs; dairy products; and rice; - Fish-seafood DP-FFQ: High intake of marine fish; shrimps, crabs, and mussels; freshwater fish; seaweed; organ meat; - Protein-sweets DP-FFQ: High intake of dairy products; milk; eggs; beans and products; nuts; pastries and candies; - Traditional DP-FFQ: High intake of vegetables; fruits; rice; nuts; Outcome and assessment methods:; GDM, OGTT assessed at: 24-28 GW; GDM diagnosed following 75g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/l | GDM; Multivariate logistic regression; OR (95% CI); [underlined: Traditional DP-TFD]; All participants; Q2 vs. Q1 (Ref): 0.69 (0.45, 1.05), p≥0.05; Q3 vs. Q1 (Ref): 0.90 (0.58, 1.42), p≥0.05; Q4 vs. Q1 (Ref): 0.40 (0.23, 0.71), p<0.05; p for trend=0.005; <35y; Q4 vs. Q1 (Ref): 0.92 (0.33, 2.52), p≥0.05; ≥35y; Q4 vs. Q1 (Ref): 0.25 (0.12, 0.52), p<0.05; [underlined: Sweet foods DP-TFD]; Q2 vs. Q1 (Ref): 0.94 (0.61, 1.44), p≥0.05; Q3 vs. Q1 (Ref): 0.90 (0.58, 1.39), p≥0.05; Q4 vs. Q1 (Ref): 0.73 (0.46, 1.16), p≥0.05; p for trend=0.199; [underlined: Fried food-beans DP-TFD]; Q2 vs. Q1 (Ref): 1.46 (0.95, 2.26), p≥0.05; Q3 vs. Q1 (Ref): 1.28 (0.82, 2.02), p≥0.05; Q4 vs. Q1 (Ref): 1.08 (0.67, 1.74), p≥0.05; p for trend=0.940; [underlined: Whole grain-seafood DP-TFD]; Q2 vs. Q1 (Ref): 1.06 (0.67, 1.68), p≥0.05; Q3 vs. Q1 (Ref): 1.49 (0.95, 2.35), p≥0.05; Q4 vs. Q1 (Ref): 1.73 (1.10, 2.74), p<0.05; p for trend=0.007; [underlined: Fish-seafood DP-FFQ]; Q2 vs. Q1 (Ref): 0.87 (0.55, 1.40), p≥0.05; Q3 vs. Q1 (Ref): 0.99 (0.61, 1.60), p≥0.05; Q4 vs. Q1 (Ref): 0.95 (0.56, 1.59), p≥0.05; p for trend=0.986; [underlined: Protein-sweets DP-FFQ]; Q2 vs. Q1 (Ref): 0.94 (0.60, 1.49), p≥.0.05; Q3 vs. Q1 (Ref): 1.23 (0.75, 2.00), p≥0.05; Q4 vs. Q1 (Ref): 1.18 (0.69, 2.03), p≥0.05; p for trend=0.434; [underlined: Traditional DP-FFQ]; All participants; Q2 vs. Q1 (Ref): 0.64 (0.42, 0.98), p<0.05; Q3 vs. Q1 (Ref): 0.40 (0.26, 0.64), p<0.05; Q4 vs. Q1 (Ref): 0.44 (0.27, 0.70), p<0.05; p for trend<0.001; <35y; Q4 vs. Q1 (Ref): 0.67 (0.31, 1.44), p≥0.05; ≥35y; Q4 vs. Q1 (Ref): 0.33 (0.18, 0.62), p<0.05; There were no modification effects for any DP by parity or pre-pregnancy BMI.; OGTT; Multivariable linear regression; β (95% CI), mmol/l; FBG; [underlined: Traditional DP-TFD]; −0.03; (−0.05, 0.00), p<0.05; [underlined: Whole-grain seafood DP-TFD]; 0.00 (−0.03, 0.03), p≥0.05; [underlined: Traditional DP-FFQ]; −0.04 (−0.06, −0.02), p<0.05; 1h BG; [underlined: Traditional DP-TFD]; −0.11 (−0.19, −0.03), p<0.05; [underlined: Whole-grain seafood DP-TFD]; 0.11 (0.02, 0.19), p<0.05; [underlined: Traditional DP-FFQ]; −0.07 (−0.13, −0.01), p<0.05; 2h BG; [underlined: Traditional DP-TFD]; −0.02 (−0.08, 0.04), p≥0.05; [underlined: Whole-grain seafood DP-TFD]; 0.04 (−0.02, 0.11), p≥0.05; [underlined: Traditional DP-FFQ]; −0.07 (−0.11, −0.02), p<0.05 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity; Other covariates: TEI; Other DP from same dietary assessment tool (TFD or FFQ); Funding: National Natural Science Foundation of China; China Scholarship Council; Summary: Greater alignment with the Traditional DP derived from both TFD and FFQ diet assessment methods was associated with a lower risk of GDM alignment with the Whole-grain seafood DP was associated with a higher risk of GDM. Alignment with the Sweet foods DP, Fried food-beans DP, Fish-seafood DP, and Protein-sweets DP were not associated with risk of GDM. Greater alignment with the Traditional DP-TFD and -FFQ was associated with lower OGTT FBG and 1h BG, but only greater alignment with the Traditional DP-FFQ was associated with lower OGTT 2h BG. Greater alignment with the whole-grain seafood DP was associated with higher OGTT 1h BG, but not OGTT FBG or 2h BG.
Mak, 2018^22^; PCS, China, Sichuan University; Analytic N =1,337; - Age (y): GDM: 26.8±4.2; Non-GDM: 25.7±4.0, p<0.001; ○ (%): ≥35: GDM: 5.0; Non-GDM: 2.4, p=0.002; - SEP:; ○ Education (%): ≤Junior secondary school: 24.0; ≥University: 36.8; - Pre-pregnancy BMI: (%): ≥24: GDM: 20.6; Non-GDM: 11.2, p<0.001; - Smoking (%): Before pregnancy: 5.5 | Plant-based DP, Meat-based DP, & High protein-low starch DP (tertiles of alignment); FFQ at: 15-20 GW; DP Descriptions:; - Plant-based DP: High intake of green leafy vegetables; cruciferous vegetables; gourd/melon family vegetables; red/orange vegetables; potatoes; root vegetables; bean vegetables; bean products; mushrooms; and fruits; Low intake of lean pork meat; - Meat-based DP: High intake of pork; pig blood curd; ox tripe; organ meat; processed meat; squid; and mushrooms; - High protein-low starch DP: High intake of eggs; milk; fish; and lean pork meat; Low intake of noodles; and bread; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following a 75g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/l | GDM; Logistic regression; OR (95% CI); [underlined: Plant-based DP]; T2 vs. T1 (Ref): 0.94 (0.62, 1.42), p=NS; T3 vs. T1 (Ref): 0.97 (0.64, 1.47), p=NS; p for trend= 0.915; No effect modification by pre-pregnancy BMI, age, or family history of DM; [underlined: Meat-based DP]; T2 vs. T1 (Ref): 1.08 (0.72, 1.62), p=NS; T3 vs. T1 (Ref): 0.89 (0.58, 1.36), p=NS; p for trend=0.534; No effect modification by pre-pregnancy BMI, age, or family history of DM; [underlined: High protein-low starch DP]; All participants; T2 vs. T1 (Ref): 0.84 (0.56, 1.26), p=NS; T3 vs. T1 (Ref): 0.73 (0.48, 1.10), p=NS; p for trend=0.132; Pre-pregnancy BMI ≥24; T2 vs. T1 (Ref): p=NS; T3 vs. T1 (Ref): 0.29 (0.09, 0.94); p for trend=0.049; No effect modification by age or family history of DM | Key confounders accounted for:; Age, Physical activity, SEP, Pre-pregnancy BMI, Parity; Other covariates: Family history of DM; Funding: China Medical Board; Summary: Greater alignment with the High protein-low starch DP was associated with lower risk of GDM among participants with pre-pregnancy BMI ≥24, but there was no association among all participants. Alignment with the Plant-based DP and Meat-based DP was not associated with risk of GDM.
Miele, 2021^25^; PCS, Brazil, Preterm SAMBA; Analytic N =1,165; - Age (y): (%): ≤19: 25.0; ≥35: 6.7; - Race/Ethnicity (%): Non-White: 60.3; White: 39.7; - SEP:; ○ Education (%): <12y: 67.9; ○ Yearly income (%): ≤$12,000: 73.9; ○ Employed (%): 50.2; - BMI at first visit (%): Overweight: 25.7; Obesity: 17.1; - History of GDM (%): 100% nulliparous | Obesogenic DP, Intermediate DP, Vegetarian DP, & Protein DP vs. Traditional DP; 24 HR at: 19-21 GW; DP Descriptions:; - Obesogenic DP: Higher in ultra-processed and processed foods using NOVA classification (refined carbohydrate; fats; sweets); - Intermediate DP: Lower consumption of same food groups as “Obesogenic DP”; - Vegetarian DP: Higher in dairy; fruits; vegetables; - Protein DP: Higher in fatty meats; eggs; beans; very low quantity of natural foods (using NOVA classification); - Traditional DP: Higher in beans; meats; eggs; natural or minimally processed foods (using NOVA classification); Outcome and assessment methods:; GDM assessed at: TM2 or TM3; Diagnosed following 75g OGTT (≥2): fasting ≥5.3, 1h ≥10.0, 2h ≥8.6 mmol/l | GDM; Multiple logistic regression; OR; [underlined: Obesogenic DP vs. Traditional DP (ref):] 1.00, p≥0.05; [underlined: Intermediate DP vs. Traditional DP (ref):] 1.46, p≥0.05; [underlined: Vegetarian DP vs. Traditional DP (ref):] 1.32, p≥0.05; [underlined: Protein DP vs. Traditional DP (ref):] 1.04, p≥0.05 | Key confounders accounted for:; Age, Race/ethnicity, SEP, Pre-pregnancy BMI, Parity, History of GDM; Other covariates: Region; Funding: Brazilian National Research Council; Bill and Melinda Gates Foundation; Summary: Alignment with the Obesogenic DP, Intermediate DP, Vegetarian DP, and Protein DP was not associated with risk of GDM when compared to the Traditional DP.
Pajunen, 2021^26^; PCS, Finland, Turku University Hospital & University of Turku; Analytic N =351; - Age (y): GDM: 31.3±4.5; No GDM: 30.3±4.5; - SEP:; ○ University or college (%): GDM: 55.0; No GDM: 65.5; - Pre-pregnancy BMI: (%): 25-29.9: GDM: 50.6; No GDM: 65.9; ≥30: GDM: 49.4; No GDM: 34.1, p=0.041; - History of GDM (%): GDM: 9.9; No GDM: 4.4; - Early pregnancy GDM (%): 0.0; - Smoking (%): Pre-pregnancy: GDM: 13.8; No GDM: 23.1 | Healthier DP & Unhealthier DP (quintiles of alignment); Food diary at: ~13 GW; DP Descriptions:; - Healthier DP: High intake of vegetables; fruits and berries; rye bread; pasta and rice; fish and seafood; coffee and tea; poultry; margarine and oils; cheeses; and eggs; - Unhealthier DP: High intake of multigrain and wheat bread; dairy desserts (e.g., ice-cream, whipped cream); sweet pastries; savory pastries; sugar, sweets and chocolate; nuts, seeds, popcorn, potato crisps and dried fruits; beverages; pasta and rice; and poultry; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 75g OGTT: fasting ≥5.3, 1h ≥10.0, or 2h ≥8.6 mmol/l | GDM; Logistic regression; OR (95% CI); [underlined: Healthier DP]; Quintile 2 vs. Quintile 1 (Ref): 0.65 (0.30, 1.41), p=0.277; Quintile 3 vs. Quintile 1 (Ref): 0.94 (0.45, 1.96), p=0.872; Quintile 4 vs. Quintile 1 (Ref): 0.27 (0.11, 0.70), p=0.007; Quintile 5 vs. Quintile 1 (Ref): 0.82 (0.38, 1.74), p=0.602; [underlined: Unhealthier DP]; Quintile 2 vs. Quintile 1 (Ref): 0.88 (0.40, 1.91), p=0.746; Quintile 3 vs. Quintile 1 (Ref): 0.74 (0.33, 1.64), p=0.458; Quintile 4 vs. Quintile 1 (Ref): 0.49 (0.21, 1.15), p=0.101; Quintile 5 vs. Quintile 1 (Ref): 1.04 (0.48, 2.22), p=0.928 | Key confounders accounted for:; Age, Physical activity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Trial group; Funding: University of Turku; Academy of Finland; Diabetes Research Foundation; Juho Vainio Foundation; Summary: Among participants with Pre-pregnancy BMI ≥25, Alignment with the fourth quintile of the Healthier DP was associated with a reduced risk of GDM compared to the first quintile of the Healthier DP. All other comparisons of the Healthier DP and Unhealthier DP quintiles was not associated with risk of GDM.
Paknahad, 2019^27^; PCS, Iran (Islamic Rep. of), Selseleh County Health Centers; Analytic N =150; - Age (y): HCLF: 27.67±6.1; HCHF: 27.70±4.1; High fiber: 29.27±5.8; - SEP:; ○ Job (%): Homemaker: HCLF: 97.1; HCHF: 96.4; High fiber: 96.7; Employed: HCLF: 2.9; HCHF: 3.6; High fiber: 3.3; - Baseline BMI: HCLF: 26.2; HCHF: 26.8; High fiber: 25.8 | HCLF DP, HCHF DP, & High fiber DP (HCLF DP & HCHF DP vs. High fiber DP); FFQ at: TM1; DP Descriptions:; - High Carbohydrate-Lower Fat (HCLF) DP: High intake of potato; fried potato; flour; egg; cooked carrots; pickles; noodle soup; beans; pomegranate; corn and maize; lentils; low-fat milk; lettuce; and raw carrot; - High Carbohydrate-Higher Fat (HCHF) DP: High intake of pea; soybean; fish; cabbage; cooked spinach; vegetable; high-fat milk; butter; tomato; cucumber; soup; cooked beans; and diluted yogurt; - High fiber DP: High intake of cantaloupe; melon; peach; nectarine; green tomatoes; plums; watermelons; pears; apricots; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 100g OGTT (≥2): fasting ≥95, 1h ≥180, 2h ≥155, 3h ≥140 mg/dL | GDM; Linear regression; OR (95% CI); [underlined: HCLF vs. High fiber (Ref):] 15.08 (1.5, 26.4), p=0.01; [underlined: HCHF vs. High fiber (Ref):] 5.4 (0.4, 61.3), p=0.18 | Key confounders accounted for:; Age, SEP, Pre-pregnancy BMI; Other covariates: Infectious diseases; TEI; Funding: NR; Summary: Alignment with the HCLF DP was associated with greater risk of GDM when compared to alignment with the High fiber DP. Alignment with the HCHF DP was not associated with risk of GDM when compared to alignment with the High fiber DP.
Radesky, 2008^28^; PCS, United States, Project Viva; Analytic N =1,733; - Age (y): 32.2±4.9; - Race/Ethnicity (%):; ○ White: 72; ○ Black: 12; ○ Other: 9; ○ Hispanic: 6; - SEP:; ○ Education (%): ≤High school diploma: 9.4; ○ Household income <$40k (%): 11.5; - Pre-pregnancy BMI (%): 25-29.9: 21; ≥30: 14; - History of GDM (%): No: 67; Yes: 2; Primiparous: 32; - Smoking (%): 3 | Prudent & Western DP (quartiles of alignment); FFQ at 11.8 (5-25.6) GW; DP Descriptions:; - Prudent DP: Higher in vegetables, fruit, legumes, fish, poultry, eggs, salad dressing, whole grains; - Western DP: Higher in red and processed meats, sugar-sweetened beverages, French fries, high-fat dairy products, desserts, butter, refined grains; Outcome and assessment methods:; GDM at: 26-28 GW; Diagnosed following 100g OGTT (≥2): fasting ≥95, 1h ≥180, 2h ≥155, 3h ≥140 mg/dL | GDM; Multinomial regression; OR (95% CI); [underlined: Western DP]; Q4 vs Q1 (Ref): 0.87 (0.41, 1.83),; Q3 vs Q1 (Ref): 1.63 (0.84, 3.19); Q2 vs Q1 (Ref): 1.14 (0.56, 2.29); p for trend=0.80; [underlined: Prudent DP]; Q4 vs Q1 (Ref): 1.13 (0.59, 2.16); Q3 vs Q1 (Ref): 1.06 (0.55, 2.05); Q2 vs Q1 (Ref): 0.56 (0.26, 1.21); p for trend=0.35; *Sensitivity analysis by excluding participants with a history of previous GDM did not alter the results | Key confounders accounted for:; Age, Race/ethnicity, Parity, Smoking, Pre-pregnancy BMI, History of GDM; Other covariates: Family history of DM; Funding: NICHD, NHLBI, NIDDK, March of Dimes Birth Defects Foundation, Harvard Medical School, Harvard Pilgrim Health Care Foundation; Summary: Alignment with the Western DP and Prudent DP was not associated with risk of GDM.
Tryggvadottir, 2016^32^; PCS, Iceland, Landspitali National University Hospital; Analytic N =168; - Age (y): ~29.5; - Pre-pregnancy BMI (%): 25-29.9: 26; ≥30: 23; - History of GDM (%): 0.0; - Smoking (%): 0.0 | Prudent DP (continuous alignment); 4-day weighed food record at 19-24 GW; DP Description:; - Prudent DP: Higher in seafood, eggs, vegetables, fruit and berries, vegetable oils, nuts and seeds, pasta, breakfast cereals, and coffee and tea; lower in soft drinks and French fries; Outcome and assessment methods:; GDM at: 23-28 GW; Diagnosed following 75g OGTT: fasting 5.1-6.9, 1h ≥10.0, or 2h 8.5–11.0 mmol/l | GDM; Logistic regression; OR (95% CI); [underlined: All participants]: 0.44 (0.21, 0.90); [underlined: Pre-pregnancy BMI >25]: 0.31 (0.13, 0.75) | Key confounders accounted for:; Age, Parity, Smoking, Pre-pregnancy BMI, History of GDM; Other covariates: TEI, Weekly GWG, Total metabolic equivalent of a task; Funding: University of Iceland, Landspitali National University Hospital; Summary: Greater alignment with the Prudent DP was associated with a lower risk of GDM among all participants and participants with pre-pregnancy BMI ≥25.
Yong, 2020^35^; PCS, Malaysia, SECOST; Analytic N =452; - Age (y): Non-GDM: 30.04±4.50; GDM: 29.80±4.39; ○ (%): ≥35: Non-GDM: 15.8; GDM: 18.7; - Race/Ethnicity (%): Malay: Non-GDM: 88.9; GDM: 89.6; Non-Malay: Non-GDM: 11.1; GDM: 10.4; - SEP:; ○ Education (y): Non-GDM: 12.93±3.53; GDM: 13.21±2.70; ○ Employed (%): Non-GDM: 68.6; GDM: 68.7; ○ Household income (%): Low: Non-GDM: 63.4; GDM: 58.3; High: Non-GDM: 2.5; GDM: 8.4, p=0.08; - Pre-pregnancy BMI (%): 25-29.9: Non-GDM: 21.8; GDM: 31.3; ≥30: Non-GDM: 11.1; GDM: 12.5; - History of GDM (%): Non-GDM: 5.7; GDM: 16.7, p=0.01 | DP 1, DP 3, DP 4, & DP 6 (tertiles of alignment); FFQ at: 9.82±2.51 GW and 12.26±1.58 GW; DP Descriptions:; - DP 1 (“Prudent, Healthy DP” at ~10 GW): Higher in green leafy vegetables; other vegetables; nuts, seeds and legumes;fruits; eggs; milk and dairy products; - DP 3 (“Western DP” at ~10 GW): Higher in rice, noodles, and pasta; oils and fats; high energy beverages; fish and seafood; sweet foods; poultry and meat; - DP 4 (“Prudent, Healthy DP” at ~12 GW): Higher in green leafy vegetables; other vegetables; nuts, seeds, and legumes; fruits; - DP 6 (“Western DP” at ~12 GW): Higher in eggs; milk and dairy products; rice, noodles, and pasta; high energy beverages; fish and seafood; sweet foods; poultry and meat; bread, cereal, and cereal products; processed meat; Outcome and assessment methods:; GDM assessed at: 28-32 GW; Diagnosed following 75g OGTT: fasting ≥5.6 and/or 2h ≥7.8 mmol/l | GDM; Generalized linear mixed model; OR (95% CI); [underlined: DP 1]; T2 vs. T1 (Ref): 0.83 (0.39, 1.76), p=0.62; T3 vs. T1 (Ref): 0.82 (0.38, 1.75), p=0.60; [underlined: DP 3]; T2 vs. T1 (Ref): 0.70 (0.33, 1.49), p=0.36; T3 vs. T1 (Ref): 0.79 (0.38, 1.64), p=0.52; [underlined: DP 4]; T2 vs. T1 (Ref): 0.78 (0.37, 1.63), p=0.51; T3 vs. T1 (Ref): 0.81 (0.38, 1.71), p=0.57; [underlined: DP 6]; T2 vs. T1 (Ref): 1.27 (0.59, 2.72), p=0.54; T3 vs. T1 (Ref): 1.15 (0.54, 2.47), p=0.72 | Key confounders accounted for:; Age, Race/ethnicity, History of GDM; Other covariates: Clinic; GW at OGTT, Family history of DM; Funding: Danone Dumex (Malaysia) Shd. Bhd.; Summary: Alignment with the DP 1 (“Prudent, Healthy DP” at ~10 GW), DP 3 (“Western DP” at ~10 GW), DP 4 (“Prudent, Healthy DP” at ~12 GW), and DP 6 (“Western DP” at ~12 GW) was not associated with risk of GDM.
Zhou, 2018^36^; PCS, China, Tongji MCHC; Analytic N =2,755; - Age (%): 17-24: 11.3; 30–35: 25.1; 36–45: 4.0; - Race/Ethnicity (%): Han: 97.4; Other: 2.6; - SEP:; ○ Education (%): ≤9y: 2.9; 10-12y: 11.5; ≥16y: 57.7; ○ Income (%): ≤1000 CNY: 0.4; 1001–2999 CNY: 6.3; ≥10000 CNY: 18.6; - Pre-pregnancy BMI: (%): 24-27.9: 9.8; ≥28: 1.5; - History of GDM (%): 0.0; - High FBG in early pregnancy (%): 0.0; - Smoking (%): 16.3 | BV DP, FME DP, NWG DP, OPS DP, & RWF DP(continuous alignment, quartiles of alignment); FFQ at: 2wk before GDM diagnosis; DP Descriptions:; - Beans-vegetables (BV) DP: Higher intake of root vegetables; mushrooms and algae; melon and solanaceous vegetables; beans and bean products (soybean, mung bean, soybean milk, bean curd, etc.); leafy and cruciferous vegetables; - Nuts-whole grains (NWG) DP: Higher intake of nuts; whole grains, dairy products; - Organ-poultry-seafood (OPS) DP: Higher intake of animal organ and blood; seafood; poultry; - Fish-meat-eggs (FME) DP: Higher intake of red meat; freshwater fish; eggs; - Rice-wheat-fruits (RWF) DP: Higher intake of rice and wheat products; fruits; Outcome and assessment methods:; GDM assessed at: 24-28 GW; Diagnosed following 75g OGTT: fasting ≥5.1, 1h ≥10.0, or 2h ≥8.5 mmol/l | GDM; Logistic regression; OR (95% CI); [underlined: BV DP]; Per SD increase: 1.04 (0.90, 1.21), p=0.592; Q2 vs. Q1 (Ref): 0.68 (0.44, 1.04), p≥0.05; Q3 vs. Q1 (Ref): 1.15 (0.78, 1.68), p≥0.05; Q4 vs. Q1 (Ref): 0.97 (0.64, 1.46), p≥0.05; p for trend=0.649; [underlined: NWG DP]; Per SD increase: 1.09 (0.94, 1.26), p=0.245; Q2 vs. Q1 (Ref): 0.83 (0.55, 1.26), p≥0.05; Q3 vs. Q1 (Ref): 0.89 (0.59, 1.35), p≥0.05; Q4 vs. Q1 (Ref): 1.25 (0.84, 1.86), p≥0.05; p for trend=0.308; [underlined: OPS DP]; Per SD increase: 1.01 (0.87, 1.17), p=0.900; Q2 vs. Q1 (Ref): 0.93 (0.63, 1.39), p≥0.05; Q3 vs. Q1 (Ref): 0.84 (0.57, 1.26), p≥0.05; Q4 vs. Q1 (Ref): 1.01 (0.68, 1.51), p≥0.05; p for trend=0.918; [underlined: FME DP]; All participants; Per SD increase: 1.32 (1.12, 1.54), p=0.001; Q2 vs. Q1 (Ref): 1.22 (0.80, 1.88), p≥0.05; Q3 vs. Q1 (Ref): 1.25 (0.81, 1.92), p≥0.05; Q4 vs. Q1 (Ref): 1.83 (1.21, 2.79), p<0.05; p for trend=0.007; Pre-pregnancy BMI <18.5; Per SD increase: 1.04 (0.68, 1.61), p=0.850; Q2 vs. Q1 (Ref): 0.99 (0.34, 2.89), p≥0.05; Q3 vs. Q1 (Ref): 0.58 (0.17, 2.01), p≥0.05; Q4 vs. Q1 (Ref): 0.95 (0.29, 3.14), p≥0.05; p for trend=0.727; Pre-pregnancy BMI 18.5-23.9; Per SD increase: 1.33 (1.09, 1.62), p=0.005; Q2 vs. Q1 (Ref): 1.26 (0.73, 2.16), p≥0.05; Q3 vs. Q1 (Ref): 1.27 (0.74, 2.17), p≥0.05; Q4 vs. Q1 (Ref): 2.02 (1.19, 3.42), p<0.05; p for trend=0.012; Pre-pregnancy BMI ≥24; Per SD increase: 1.62 (1.12, 2.34), p=0.010; Q2 vs. Q1 (Ref): 1.18 (0.41, 3.43), p≥0.05; Q3 vs. Q1 (Ref): 2.22 (0.79, 6.21), p≥0.05; Q4 vs. Q1 (Ref): 2.84 (1.03, 7.80), p<0.05; p for trend=0.021; Family history of DM; Per SD increase: 1.73 (1.11, 2.69), p=0.015; Q2 vs. Q1 (Ref): 1.97 (0.55, 7.10), p≥0.05; Q3 vs. Q1 (Ref): 0.72 (0.17, 3.10), p≥0.05; Q4 vs. Q1 (Ref): 3.38 (1.05, 10.90), p<0.05; p for trend=0.068; No family history of DM; Per SD increase: 1.27 (1.07, 1.51), p=0.005; Q2 vs. Q1 (Ref): 1.16 (0.73, 1.84), p≥0.05; Q3 vs. Q1 (Ref): 1.34 (0.85, 2.12), p≥0.05; Q4 vs. Q1 (Ref): 1.68 (1.06, 2.66), p<0.05; p for trend=0.023; [underlined: RWF DP]; All participants; Per SD increase: 0.78 (0.68, 0.88), p<0.001; Q2 vs. Q1 (Ref): 0.87 (0.60, 1.26), p≥0.05; Q3 vs. Q1 (Ref): 0.54 (0.36, 0.83), p<0.05; Q4 vs. Q1 (Ref): 0.72 (0.48, 1.08), p≥0.05; p for trend=0.010; Pre-pregnancy BMI <18.5; Per SD increase: 0.49 (0.30, 0.82), p=0.007; Q2 vs. Q1 (Ref): 0.90 (0.30, 2.66), p≥0.05; Q3 vs. Q1 (Ref): 0.75 (0.23, 2.47), p≥0.05; Q4 vs. Q1 (Ref): 0.35 (0.10, 1.20), p≥0.05; p for trend=0.114; Pre-pregnancy BMI 18.5-23.9; Per SD increase: 0.79 (0.68 0.91), p=0.002; Q2 vs. Q1 (Ref): 0.94 (0.60, 1.49), p≥0.05; Q3 vs. Q1 (Ref): 0.47 (0.27, 0.80), p<0.05; Q4 vs. Q1 (Ref): 0.77 (0.46, 1.27), p≥0.05; p for trend=0.039; Pre-pregnancy BMI ≥24; Per SD increase: 0.88 (0.64 1.22), p=0.447; Q2 vs. Q1 (Ref): 0.49 (0.18, 1.35), p≥0.05; Q3 vs. Q1 (Ref): 0.73 (0.29, 1.87), p≥0.05; Q4 vs. Q1 (Ref): 0.95 (0.36 2.53), p≥0.05; p for trend=0.636; Family history of DM; Per SD increase: 0.82 (0.67, 1.02), p=0.070; Q2 vs. Q1 (Ref): 0.85 (0.27, 2.62), p≥0.05; Q3 vs. Q1 (Ref): 1.43 (0.49, 4.18), p≥0.05; Q4 vs. Q1 (Ref): 1.23 (0.37, 4.08), p≥0.05; p for trend=0.636; No family history of DM; Per SD increase: 0.74 (0.65, 0.85), p<0.001; Q2 vs. Q1 (Ref): 0.85 (0.57, 1.27), p≥0.05; Q3 vs. Q1 (Ref): 0.47 (0.29, 0.75), p<0.05; Q4 vs. Q1 (Ref): 0.65 (0.42, 1.00), p≥0.05; p for trend=0.005 | Key confounders accounted for:; Age, Physical activity, Race/ethnicity, SEP, Pre-pregnancy BMI, Smoking, Parity, History of GDM; Other covariates: Other DP; Family history of DM; Family history of obesity; Alcohol; GWG before GDM diagnosis; TEI; Funding: National Program on Basic Research Project of China; the Dietary Nutrition Research and Education Foundation of Danone Nutrition Center in China; Summary: Greater alignment with the FME DP was associated with a greater risk of GDM in all participants; participants with pre-pregnancy BMI 18.5-23.9 and ≥24; and participants with (association slightly attenuated) and without a family history of DM, but not among participants with pre-pregnancy BMI <18.5. Greater alignment with the RWF DP was associated with a reduced risk of GDM in all participants; participants with pre-pregnancy BMI <18.5 (association slightly attenuated) and 18.5-23.9; and participants with no family history of DM, but not among participants with pre-pregnancy BMI ≥24 or participants with family history of DM. Alignment with the BV DP, NWG DP, and OPS DP was not associated with risk of GDM.

a Abbreviations: $#K: # thousands of dollars; ADA: American Diabetes Association; AHEI: Alternative Healthy Eating Index; AHEI-P: Alternate Healthy Eating Index for Pregnancy; aMed: alternate Mediterranean Diet; aOR: adjusted odds ratio; BIGCS: Born in Guangzhou Cohort Study; BMI: body mass index; CDGCI-PW: Chinese Dietary Guidelines Compliance Index for Pregnant Women; CI: confidence interval; DASH: Dietary Approaches to Stop Hypertension; DHA: Docosahexaenoic acid; DM: diabetes mellitus; DP: dietary pattern(s); EPA: Eicosapentaenoic acid; EVOO: extra virgin olive oil; FFQ: food frequency questionnaire; FPL: Federal poverty level; g: gram(s); GDM: gestational diabetes mellitus; GRMRS: Gestational Diabetes in the Mediterranean Region Study; GW: gestational weeks; GWG: gestational weight gain; h: hour(s); HDP: hypertensive disorders of pregnancy; HEI: Healthy Eating Index; HFII: Healthy Food Intake Index; HTN: hypertension; IADPSG: International Association of the Diabetes and Pregnancy Study Groups; l: liter; MDI: Mediterranean Diet Index; MDS: Mediterranean diet score; MEDAS: Mediterranean Diet Adherence Screener; MedDiet: Mediterranean diet; mmol: millimole; mo: month; MUFA: monounsaturated fatty acid; NFFD: Norwegian Fit for Delivery; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Development; NIH: National Institutes of Health; NR: not reported; NS: non-significant; OGTT: oral glucose tolerance test; OR: odds ratio; PCA: principal component analysis; PCS: prospective cohort study; PDI: Plant-based Diet Index; PUFA: polyunsaturated fatty acid; Q#: quartile; RCT: randomized controlled trial; Ref: reference; SD: standard deviation; SEP: SEP; SFA: saturated fatty acid; T#: tertile; TEI: total energy intake; TFD: Three-day food diary; TG: triglycerides; week(s); y: year(s)

Table 8 Risk of bias for randomized controlled trials examining dietary patterns consumed during pregnancy and gestational diabetes mellitus^a^

Article | Randomization | Deviations from intended interventions effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Al Wattar, 2019^37^ | LOW | LOW | LOW | LOW | LOW | LOW
Assaf-Balut, 2017^38^ (24-28 GW) | LOW | LOW | LOW | LOW | HIGH | HIGH
Assaf-Balut, 2017^38^ (36-38 GW) | LOW | HIGH | LOW | LOW | HIGH | HIGH
Assaf-Balut, 2019^39^ | LOW | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Dodd, 2019^40^ | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS
Melero, 2020^41^ (24-28 GW) | LOW | LOW | LOW | LOW | HIGH | HIGH
Melero, 2020^41^ (36-38 GW) | LOW | HIGH | LOW | LOW | HIGH | HIGH
Papandreou, 2023^42^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Van Horn, 2018^43^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zhao, 2022^44^ (24-28 GW) | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Zhao, 2022^44^ (36-38 GW) | LOW | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898 31462531

Table 9 Risk of bias for non-randomized controlled trials examining dietary patterns consumed during pregnancy and gestational diabetes mellitus^a^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Melero, 2020^41^ (24-28 GW) | LOW | LOW | LOW | LOW | LOW | LOW | SERIOUS | SERIOUS
Melero, 2020^41^ (36-38 GW) | LOW | LOW | SERIOUS | SERIOUS | LOW | LOW | SERIOUS | SERIOUS

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919 27733354 .)

Table 10 Risk of bias for observational studies examining dietary patterns consumed during pregnancy and gestational diabetes mellitus^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Angali, 2020^1^ | SOME CONCERNS | SOME CONCERNS | HIGH | LOW* | HIGH | LOW | HIGH | VERY HIGH
Assaf-Balut, 2018^2^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Badon, 2017^3^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Bernier, 2023^4^ | HIGH | LOW | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
de Seymour, 2022^5^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ding, 2021^6^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Du, 2017^7^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Flor-Alemany, 2021^8^ | SOME CONCERNS | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Flor-Alemany, 2022^9^ | HIGH | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Flynn, 2016^10^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Fulay, 2018^11^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hajianfar, 2018^12^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
He, 2015^13^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Hehua, 2021^14^ | LOW* | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Hillesund, 2018^15^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hrolfsdottir, 2019^16^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Hu, 2019^17^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | HIGH | LOW | HIGH | HIGH
Karamanos, 2014^18^ | HIGH | HIGH | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Li, 2021^19^ | LOW | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Lindsay, 2020^20^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Lindsay, 2022^21^ | HIGH | LOW | LOW | LOW | HIGH | SOME CONCERNS | HIGH | HIGH
Mak, 2018^22^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Makarem, 2022^23^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | SOME CONCERNS | HIGH | HIGH
Meinila, 2017^24^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Miele, 2021^25^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Pajunen, 2021^26^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Paknahad, 2019^27^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Radesky, 2008^28^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | LOW | HIGH
Rifas-Shiman, 2009^29^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ruiz-Gracia, 2016^45^ | HIGH | VERY HIGH | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Sauder, 2016^30^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Tranidou, 2023^31^ | HIGH | LOW | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Tryggvadottir, 2016^32^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wang, 2021^33^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Yee, 2020^34^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | SOME CONCERNS | HIGH | HIGH
Yong, 2020^35^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | LOW | HIGH
Zhou, 2018^36^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( ROBINS-E Development Group (Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi:10.1016/j.envint.2024.108602 ). *Low risk of bias except for concerns about uncontrolled confounding.