# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 3 systematic reviews assessing the relationship between dietary patterns and GDM, hypertensive disorders of pregnancy,^*^ and type 2 diabetes mellitus.^†^ Literature search A (Appendix 4) regarding dietary patterns and GDM and hypertensive disorders of pregnancy yielded 665 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 483 titles, 89 abstracts, and 74 full-text articles. Literature search B (Appendix 4) regarding dietary patterns and GDM and type 2 diabetes yielded 13,479 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 11,337 titles, 1,384 abstracts, and 653 full-text articles. Reasons for full-text exclusion are in Appendix 5. Five additional articles were identified from the existing systematic review^‡^ and 4 additional articles were identified from the manual search. The body of evidence included 45 articles.

* Byrd-Bredbenner C, Abrams SA, Andres A, . Dietary Patterns Consumed During Pregnancy and Risk of Hypertensive Disorders of Pregnancy: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR08

† Talegawkar S, Tobias D, Hoelscher DM, . Dietary Patterns and Risk of Type 2 Diabetes: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR12

‡ Raghavan R, Dreibelbis C, Kingshipp BJ, . Dietary Patterns before and during Pregnancy and Risk of Gestational Diabetes Mellitus: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0102

Figure 2 Literature search and screen flowchart

Literature search A in PubMed, Embase, Cochrane, and CINAHL yielded 665 search results after the removal of duplicates. Dual-screening resulted in the exclusion of 483 titles, 89 abstracts, and 74 full-text articles. 17 articles were ultimately included from search A. Literature search B in PubMed, Embase, Cochrane, and CINAHL yielded 13,479 search results after the removal of duplicates. Dual-screening resulted in the exclusion of 11,337 titles, 1,384 abstracts, and 653 full-text articles. 19 articles were ultimately included from search B. Five additional articles were identified from the existing systematic review and 4 additional articles were identified from the manual search. The body of evidence included 45 articles.

## Description of the evidence

This systematic review included 45 articles from 36 studies, including 36 articles from 28 prospective cohort studies (PCS),^1–36^ 8 articles from 6 randomized controlled trials (RCT),^37–44^ 1 article from 1 non-randomized controlled trial (NRCT),^41^ and 1 article from 1 retrospective cohort study (RCS),^45^ that address the relationship between dietary patterns during pregnancy and risk of gestational diabetes mellitus (see Table 7). Articles were from countries classified as high or very high on the Human Development Index^*^, published between January 1980 and May 2023, and enrolled participants during pregnancy who were generally healthy, including those with overweight and obesity.

* The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

The analytic sample size for RCT and NRCT ranged from 40 to 974, although 40 participants was an outlier^42^ and the rest of the trials included at least 200 participants. For cohort studies, the analytic sample size ranged from 103 to more than 8,000, but most had approximately 500 participants or more.^1–3,^ ^5–7,^ ^10–19,^ ^21–23,^ ^25,^ ^28–31,^ ^33,^ ^34,^ ^36,^ ^45^

Ten articles from 8 studies were conducted in China^5–7,^ ^13,^ ^14,^ ^17,^ ^22,^ ^33,^ ^36,^ ^44^; 11 articles from 7 studies were conducted in the U.S.^3,^ ^11,^ ^19–21,^ ^23,^ ^28–30,^ ^34,^ ^43^; 7 articles from 3 studies were conducted in Spain^2,^ ^8,^ ^9,^ ^38,^ ^39,^ ^41b,^ ^45^; 3 studies in Iran^1,^ ^12,^ ^27^; 2 studies each in Finland,^24,^ ^26^ Greece,^31,^ ^42^ Iceland,^16,^ ^32^ and the U.K.^10,^ ^37^; and 1 study each in Australia,^40^ Brazil,^25^ Canada,^4^ Malaysia,^35^ Norway,^15^ and a group of countries in the Mediterranean region.^18^

### Participant characteristics

#### Age

When reported, the mean or median age of participants ranged from approximately 26 to 34 years.^1–11,^ ^13–16,^ ^18–24,^ ^26–35,^ ^37–44^ One article only reported a range of 20-40 years as included ages of participants.^12^ One RCT reported that approximately 3.5% of participants were older than 40 years^37^ and 4 articles reported approximately 35%,^45^ 28%,^31^ and 15%^17,^ ^35^ of participants were older than 35 years. About one-third of articles excluded participants younger than 20 years,^7,^ ^12,^ ^27^ 18 years,^3,^ ^6,^ ^15,^ ^19,^ ^20,^ ^22,^ ^31,^ ^42–44^ or 16 years.^37^ One article from China^36^ included participants as young as 17 years and another conducted in Brazil reported 25% of participants were 19 years old or younger.^25^

#### Health status

##### Pre-pregnancy BMI

Most articles enrolled participants predominantly without overweight or obesity, that is, with pre-pregnancy or early pregnancy (first trimester or early second trimester) BMI <25 kg/m^2†^,^1–4,^ ^8,^ ^9,^ ^11,^ ^12,^ ^15,^ ^16,^ ^18–20,^ ^25,^ ^28,^ ^29,^ ^31,^ ^32,^ ^35,^ ^38–42,^ ^45^ <24 kg/m^2^ (using Chinese Obesity Working Group ethnicity-specific cutoffs^‡^),^7,^ ^13,^ ^14,^ ^22,^ ^33,^ ^36,^ ^44^ or <23 kg/m^2^ (using World Health Organization ethnicity-specific cutoffs^§^).^5,^ ^6,^ ^17^ One trial conducted in Greece specifically excluded participants with pre-pregnancy BMI ≥30 kg/m^2^.^42^ One-fifth of the articles enrolled participants exclusively^10,^ ^26,^ ^43^ or predominantly^21,^ ^23,^ ^24,^ ^27,^ ^30,^ ^34,^ ^37^ with pre-pregnancy or early pregnancy BMI ≥30 kg/m^210,^ ^24,^ ^37,^ ^43^ or ≥25 kg/m^2^.^21,^ ^23,^ ^26,^ ^27,^ ^30,^ ^34^

† World Health Organization. Obesity: preventing and managing the global epidemic. World Health Organ Tech Rep Ser. 2000;894:i–xii, 1–253 11234459 .

‡ Zhou BF. Predictive values of body mass index and waist circumference for risk factors of certain related diseases in Chinese adults--study on optimal cut-off points of body mass index and waist circumference in Chinese adults. BES. 2002 Mar 1;15(1):83–96 12046553 .

§ WHO Expert Consultation. Appropriate body-mass index for Asian populations and its implications for policy and intervention strategies. The Lancet. 2004;363(9403):157–163. doi: 10.1016/S0140-6736(03)15268-3

##### History of GDM

Eleven articles enrolled 1-7% of participants with a history of GDM.^2,^ ^3,^ ^26,^ ^28,^ ^30,^ ^35,^ ^37–39,^ ^41,^ ^44^ One article from Finland specifically enrolled participants at high risk for GDM and reported approximately 40% of participants had a previous GDM diagnosis.^24^ One article included participants with a history of GDM, but they did not report the prevalence.^18^ Eight articles exclusively enrolled nulliparous participants or excluded those with a previous GDM diagnosis,^15,^ ^19,^ ^21,^ ^23,^ ^25,^ ^33,^ ^34,^ ^36^ although Li et al.^19^ only excluded those with a history of GDM if their pre-pregnancy BMI was <30 kg/m^2^.^19^ An additional article reported 70.5% of participants had no history of miscarriage, GDM, or gestational hypertension.^45^ Five articles excluded those with diabetes mellitus before enrollment^1,^ ^14,^ ^31,^ ^42,^ ^43^ and 1 excluded those with previous pregnancy resulting in delivery <32 gestational weeks (GW).^5^ The remaining articles did not report on history of any type of diabetes mellitus.^4–13,^ ^16,^ ^17,^ ^20,^ ^22,^ ^27,^ ^29,^ ^32,^ ^40^

#### Race and/or ethnicity

About one-third of articles did not report race and/or ethnicity.^6–9,^ ^12,^ ^13,^ ^16,^ ^18,^ ^22,^ ^24,^ ^26,^ ^27,^ ^31,^ ^32,^ ^42,^ ^44,^ ^45^

##### White

Fifteen articles reported participants were predominantly White (64-97%).^2–4,^ ^10,^ ^11,^ ^15,^ ^21,^ ^23,^ ^28,^ ^29,^ ^34,^ ^38–40,^ ^43^

##### Asian

Seven articles reported 1-44% of participants were Asian,^9,^ ^10,^ ^21,^ ^23,^ ^34,^ ^37,^ ^40^ with 1 trial additionally specifying ~8% of participants were of South Asian ethnicity.^40^ One article only reported participant characteristics by the first and fourth quartile of alignment with a dietary pattern and reported approximately 20% of participants were Asian American or Pacific Islander.^19^ Five articles reported 78-98% Han ethnicity participants^5,^ ^14,^ ^17,^ ^33,^ ^36^ and 1 additional article reported approximately 89% Malay ethnicity participants.^35^

##### Hispanic

Twelve articles reported 6-43% Hispanic ethnicity participants.^2,^ ^11,^ ^19–21,^ ^23,^ ^28,^ ^30,^ ^34,^ ^38,^ ^39,^ ^43^. One additional trial included 100% Hispanic participants.^41^

##### Black

Nine articles reported 2-24% of participants were Black.^10,^ ^19,^ ^21,^ ^23,^ ^28,^ ^30,^ ^34,^ ^37,^ ^43^ Again, 1 article only reported participant characteristics by the first and fourth quartile of alignment with a dietary pattern and reported approximately 30% of participants were Black.^19^

##### Other

One article from Brazil reported that the majority of participants were not White,^25^ but provided no additional information about participant race and/or ethnicity. One article reported that participants were exclusively Arab ethnicity.^1^ No articles reported American Indian or Alaska Native participants.

#### SEP

##### Education

One-fifth of the articles did not report education level of participants.^18,^ ^20,^ ^27,^ ^31,^ ^32,^ ^37,^ ^40,^ ^42,^ ^45^ In most articles that did report education data, the majority of participants had at least some higher education or were described as “well educated”.^1,^ ^2,^ ^4–9,^ ^13–17,^ ^19,^ ^21,^ ^23,^ ^24,^ ^26,^ ^28–30,^ ^33–36,^ ^38,^ ^39,^ ^43^ One article reported 98% of participants had at least a high school education,^3^ while 7 articles reported that most participants had a high school education or less.^10–12,^ ^22,^ ^25,^ ^41,^ ^44^

##### Income, Occupation, or Other

One-third of the articles did not report on income, occupation, or another measure of SEP.^3,^ ^7,^ ^16,^ ^18,^ ^19,^ ^22–24,^ ^26,^ ^31,^ ^32,^ ^37,^ ^45^ Of the 19 articles that reported income, most stated that a majority of participants had at least a “middle” income according to income level cutoffs specific to each country,^4–6,^ ^11,^ ^13,^ ^15,^ ^28,^ ^29,^ ^33,^ ^36,^ ^43^ although 2 of these articles described approximately 40% of participants as “lower income.” ^6,^ ^33^ The majority of participants were below “middle” income in 4 articles conducted in Iran, China, Brazil, and Malaysia.^1,^ ^17,^ ^25,^ ^35^ An additional article reported approximately 30% were below “middle” income, but about one-third of the data were missing.^30^ Two articles from the U.S. reported income in relation to the Federal poverty level; nearly 12% of participants had incomes below the Federal poverty level^21^ and approximately 23% had incomes below 200% the Federal poverty level,^34^ respectively. One article reported unclear income levels.^14^

Of the 15 articles that reported occupation, 12 described participants as mostly employed.^2,^ ^8,^ ^9,^ ^12,^ ^15,^ ^25,^ ^30,^ ^35,^ ^38,^ ^39,^ ^42,^ ^44^ Three articles conducted in Spain and Iran noted that participants were mostly unemployed.^1,^ ^27,^ ^41^

Five articles reported a SEP measure other than education, income, or occupation. One Australian trial noted that approximately 17% of the participants were classified as most disadvantaged based on the Socio-economic Index for Areas—Index of Relative Socio-economic Disadvantage,^40^ while the mean socioeconomic status (SES) index in another article was 3.23±0.93 (scale of 1-5).^20^ In an article from the U.K., 43% of participants were classified as “most deprived” on an index of multiple deprivation.^10^ In a fourth article, the majority of participants were classified as “moderate” socioeconomic status or above.^12^ Finally, approximately 26% of participants had public insurance in an article from the U.S.^34^

#### Smoking

One-third of the articles did not describe smoking status of participants.^4–6,^ ^10,^ ^12,^ ^13,^ ^18,^ ^24,^ ^25,^ ^27,^ ^29,^ ^35,^ ^37,^ ^45^ A range of 1-11% of participants smoked during pregnancy in 18 articles^2,^ ^3,^ ^8,^ ^9,^ ^11,^ ^14–16,^ ^20,^ ^28,^ ^30,^ ^31,^ ^38–42,^ ^44^ and an additional article conducted in China reported 16.3% of participants smoked during pregnancy.^36^ Six articles stated 2-25% of participants had ever smoked or smoked before pregnancy^17,^ ^21,^ ^22,^ ^26,^ ^33,^ ^42^ and an additional 4 articles conducted in Spain and the U.S., reported approximately 40% of participants had ever smoked or smoked before pregnancy.^8,^ ^9,^ ^23,^ ^34^ Partner smoking status was reported in 1 article from China; 46% of participants had a partner who smokes.^7^ Four articles excluded participants who smoked,^1,^ ^19,^ ^32,^ ^43^ although 1 of these articles only excluded participants who smoked if their pre-pregnancy BMI was <30 kg/m^2^.^19^

### Intervention/exposures and comparators

Dietary pattern (DP) was defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they were habitually consumed.

Dietary patterns were assessed using experimental diets in 8 articles from 6 RCT and 1 NRCT,^37–44^ index/score analysis in 22 articles,^2–4,^ ^6,^ ^8,^ ^9,^ ^11,^ ^15,^ ^16,^ ^18–21,^ ^23,^ ^24,^ ^29–34,^ ^45^ and factor/cluster analysis in 16 articles.^1,^ ^5,^ ^7,^ ^10,^ ^12–14,^ ^17,^ ^22,^ ^25–28,^ ^32,^ ^35,^ ^36^ The dietary pattern components are detailed in Table 5 and visualized in Appendix 6.

Table 5 Dietary Pattern Components^*^ * Abbreviations: DASH: Dietary Approaches to Stop Hypertension; DHA: docosahexaenoic acid; DP: dietary pattern; EPA: eicosapentaenoic acid; EVOO: extra virgin olive oil; FA: fatty acids; FFQ: food frequency questionnaire; MUFA: monounsaturated fatty acids; PUFA: polyunsaturated fatty acids; SFA: saturated fatty aicds; SSB: sugar-sweetened beverages; TFD: Three-day food diary

Reference | Dietary pattern | Dietary pattern components
Experimental Diet
Al Wattar, 2019^37^ | Mediterranean-style supplemented w/ mixed nuts and EVOO | Positive: Olive oil (as main fat and servings/d); Nuts (including peanuts) Vegetables; Fruit (including juice); Pulses; Fish or shellfish; White meat over red meat; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial sweets or pastries
Assaf-Balut, 2017^38^; Assaf-Balut, 2019^39^ | Mediterranean-style supplemented w/ pistachios and EVOO | Positive: Olive oil (as main fat and servings/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries
Dodd, 2019^40^ | Healthy Eating Index | Positive: Vegetables; fruit; dairy
Melero, 2020^41^ | Mediterranean-style supplemented w/ pistachios and EVOO | Positive: vegetables; dishes with tomato sauce (tomato, garlic, onion, leek, olive oil); pulses; nuts; fish; white meat over red meat; olive oil; olive oil as principal cooking fat.; Negative: commercial pastries; red meat or sausages; animal fat; sugar-sweetened beverages; Alcohol and fruit (including juice) components excluded
Papandreou, 2023^42^ | Mediterranean-style | Positive: Vegetables; potatoes; legumes; fruit; whole grains; fish; olive oil; Negative: Red and processed meat; poultry; full-fat dairy; alcohol
Van Horn, 2018^43^ | DASH-style | Positive: Vegetables (not potatoes); nuts and legumes; fruit (including fruit juice); whole grains; low-fat dairy; Negative: Red and processed meat; sweetened beverages; sodium
Zhao, 2022^44^ | Mediterranean-style w/ recommended additional pistachios and EVOO | Positive: Olive oil (as main fat and servings/d); Vegetables; Fruit (including juice); Red wine; Pulses; Fish/seafood; Nuts; White over red meat; Traditional sauce of tomatoes, garlic, onion, or leeks sautéed in olive oil; Negative: Red or processed meat; Butter, margarine, or cream; SSB; Commercial pastries
Index/Score Analysis
Assaf-Balut, 2018^2^ | Modified Mediterranean Diet Adherence Screener | Positive: EVOO (daily and weekly); Nuts; Vegetables; Whole fruits (excluding juice); Negative: Juice
Badon, 2017^3^ | Alternative Healthy Eating Index-2010 | Positive: vegetables (not potatoes, French fries); fruit; legumes and nuts; whole grains; long-chain fats (EPA + DHA); PUFA; Negative: red and processed meat; SSB and fruit juice; trans FA; sodium; Alcohol component excluded
Bernier, 2023^4^ | Alternative Healthy Eating Index-2010 | Positive: vegetables, fruit, whole grains, nuts and legumes, long-chain (n-3) fats, PUFA; Negative: SSB and fruit juices, red/processed meat, trans fats, sodium; Alcohol component excluded
Ding, 2021^6^ | Chinese Dietary Guidelines Compliance Index for Pregnant Women | Positive: staple foods (cereals and their products, potatoes, and beans other than soybeans); green leafy and colored vegetables (red and yellow); milk and its products (milk, yogurt, formula milk powder); soybean and its products; nuts; lean meat (livestock and poultry meat); animal blood and liver; iodized table salt, iodine-rich seafood; Negative: pickled food, fried food, cream cake, chocolate, other high-salt, high-oil, and high-sugar food
Flor-Alemany, 2021^8^ | Mediterranean Diet Score | Positive: Vegetables; Potatoes; Legumes; Fruits; Whole Grains; Fish; Olive Oil; Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol component excluded
Flor-Alemany, 2022^9^ | Mediterranean Diet Score | Positive: Vegetables; Potatoes; Legumes; Fruits; Whole Grains; Fish; Olive Oil; Negative: Red and Processed Meat; Poultry; Full-Fat Dairy; Alcohol component excluded
Fulay, 2018^11^ | DASH | Positive: fruit (including fruit juice); vegetables (not potatoes); whole grains; nuts/legumes; low-fat dairy; Negative: sodium; SSB; red and/or processed meats
Fulay, 2018^11^ | DASH OMNI | Positive: fruit (including fruit juice); vegetables (not potatoes); whole grains; nuts/legumes; low-fat dairy; MUFA and PUFA; Negative: sodium; SSB; red and/or processed meats
Hillesund, 2018^15^ | Norwegian Fit For Delivery | Positive: regular meals; drinking water when thirsty; vegetables w/ dinner; fruits and vegetables btw meals; reading nutrition labels before buying; Negative: sweets and snacks without appreciation; large portion sizes of unhealthy foods; added sugar; salt; eating beyond satiety
Hrolfsdottir, 2019^16^ | Dietary risk score (reverse scored) | Positive: Non-varied diet; SSB/artificially sweetened beverages; Sweets, ice cream, cakes, cookies; Processed meat; Negative: Whole grain products; Dairy; Vitamin D
Karamanos, 2014^18^ | Mediterranean Diet Index | Positive: bread, cereals, legumes, vegetables, fruits, fish, olive oil:animal fat, potatoes,; Negative: meat, eggs, cheese, dairy products
Li, 2021^19^ | Alternative Healthy Eating Index | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA; Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Sodium; Alcohol and trans-fat components excluded
Li, 2021^19^ | Alternate Mediterranean Diet | Positive: Vegetables; Fruit; Nuts; Fish; Lean Meat (poultry, lean beef); Negative: Red and Processed Meat; Sodium.; Neutral: Grains and Starches; Dairy Foods; Alcohol component excluded
Li, 2021^19^ | DASH | Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; Negative: Red and Processed Meat; Sweetened Beverages; Sodium
Lindsay, 2020^20^ | Mediterranean Diet Score | Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA:SFA; Negative: Red and Processed Meat; Dairy Products; Alcohol component excluded
Lindsay, 2022^21^ | Alternative Healthy Eating Index-2010 | Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA.; Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium.; Moderate: Alcohol
Makarem, 2022^23^ | Alternate Mediterranean Diet | Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA:SFA; Negative: Red and Processed Meat; Moderate: Alcohol
Meinila, 2017^24^ | Healthy Food Intake Index | Positive: Vegetables; fruits and berries; fish; high-fiber grains; vegetable oils as cooking fat; oil-based fat spreads; Negative: Snacks; SSB; fast food
Rifas-Shiman, 2009^29^ | Alternative Healthy Eating Index for Pregnancy | Positive: vegetables, fruit, white meat (poultry or fish):red meat, fiber, PUFA:SFA, and folate, calcium, and iron from foods; Negative: trans fat
Ruiz-Gracia, 2016^45^ | Nutrition variables at risk | Positive: Nuts; Negative: High glucose-load refined cereals; Juices and/or sweetened drinks; Biscuit and pastries
Sauder, 2016^30^ | Healthy Eating Index-2005 | Positive: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit (including juice); Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils; Negative: SFA; Sodium; Calories from solid fats, alcohol, and added sugars
Tranidou, 2023^31^ | Mediterranean Diet Score | Positive: Vegetables; Legumes; Fruit and Nuts; Cereals; Fish; MUFA:SFA; Negative: Red and Processed Meat; Dairy Products; Moderate: Alcohol
Tranidou, 2023^31^ | Modified Mediterranean Diet Score | Positive: Vegetables (not potatoes); Legumes and nuts; Fruits; Whole grain cereals; Lean meat; Fish and shellfish; Low fat and fermented dairy products; Olive and canola oil; Olives; Negative: Fatty meat and processed meat; Full fat dairy products not fermented; Sugar; Wine component excluded
Tryggvadottir, 2016^32^ | Icelandic Healthy Eating Index | Positive: fish and seafood; vegetables; fruits; vegetable oils; nuts and seeds; unground/whole ground cereals; vitamin D; Negative: soft drinks
Wang, 2021^33^ | Plant-based diet index | Positive: plant food groups (whole grains, refined grains, fruits, vegetables, nuts, beans, vegetable oil, sweets and desserts); Negative: animal food groups (dairy products, eggs, meat and fish)
Wang, 2021^33^ | Healthy plant-based diet index | Positive: healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); Negative: less healthy plant-based foods (fruit juices, refined grains, potatoes, SSB, sweets/desserts); animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods)
Wang, 2021^33^ | Unhealthy plant-based diet index | Positive: less healthy plant-based foods (fruit juices, refined grains, potatoes, SSB, sweets/desserts); Negative: healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods)
Yee, 2020^34^ | Healthy Eating Index-2010 | Positive: Total Vegetables; Greens and Beans; Total Fruit (including juice); Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids; Negative: Refined Grains; Empty Calories (i.e., energy from solid fats, alcohol, and added sugars); Sodium
Factor/Cluster Analysis
Angali, 2020^1^ | High fat-fast food | Higher intake of pasta, vermicelli, broken wheat, high-fat organ meats, salami, sausage, high -fat dairy, and sugary cool drinks
Angali, 2020^1^ | Vegetable-fruits and protein | Higher intake of vegetable oil, fruit body vegetables, seasonal & non seasonal fruits and low-fat dairy and meat (red and white)
de Seymour, 2022^5^ | Fish, poultry and vegetables-based | Higher intake of fish; poultry; legumes and bean products; green leafy vegetables; root vegetables; other vegetables; seafood; fruits; eggs; organ meats; beverages; bread; dairy; soup; nuts
de Seymour, 2022^5^ | Pasta, sweetened beverages, oils and condiments-based | Higher intake of pasta; sweetened beverages; oils and condiments; fast food
Du, 2017^7^ | Western | Higher intake of dairy; baked/fried food; white meat
Du, 2017^7^ | Traditional | Higher intake of light-colored vegetables; fine grain; red meat; tubers
Du, 2017^7^ | Mixed | Higher intake of edible fungi; shrimp/shellfish; red meat
Du, 2017^7^ | Prudent | Higher intake of dark-colored vegetables; deep-sea fish
Du, 2017^7^ | DP 1 | Higher intake of red meat; light-colored vegetables; fine grain
Du, 2017^7^ | DP 2 | Higher intake of dark-colored vegetables; freshwater fish; fine grain
Du, 2017^7^ | DP 3 | Higher intake of dairy products; baked/fried food
Du, 2017^7^ | DP 4 | Higher intake of white meat; tubers
Flynn, 2016^10^ | Fruit & Veg | Higher intake of bananas; citrus fruit; dried fruit; fresh fruit; green vegetables; pulses; root vegetables; salad vegetables; tropical fruit; yoghurt
Flynn, 2016^10^ | African/Caribbean | Higher intake of red meat; cassava; white meat; rice including pilau, fried or jollof rice; plantain; fish
Flynn, 2016^10^ | Processed | Higher intake of chocolate; crisps; green vegetables; potatoes; processed meat and meat products; root vegetables; squash and fizzy drinks; sugar free squash and fizzy drinks; chips
Flynn, 2016^10^ | Snacks | Higher intake of biscuits and cookies; cakes and pastries; chocolate; full fat cheese; sweets
Hajianfar, 2018^12^ | Healthy | Higher intake of green vegetables, leafy vegetables, colored vegetables, fruits, low fat dairy, poultry, bulky vegetables, red meat, citrus, nuts, fish, olive, marinades, sweet fruit, egg, and unsaturated fat
Hajianfar, 2018^12^ | Western | Higher intake of processed meats, fruits, fruits juice, citrus, nuts, fish, desserts and sweets, sugar, saturated fat, sweet fruit (melon, persimmon, date, fig, grapes, raisins, berries that have high glycemic index), potato, legumes, coffee, egg, pizza, high fat dairy, whole grain, and soft drinks
Hajianfar, 2018^12^ | Traditional | Higher intake of refined grains, colored vegetables, olive, sugar, salt, spices, unsaturated fat, garlic, onion, and tea
He, 2015^13^ | Vegetable | Higher intake of root vegetables, beans, mushrooms, melon vegetables, seaweed, other legumes, fruits, leafy and cruciferous vegetables, processed vegetables, nuts, cooking oil
He, 2015^13^ | Protein-rich | Higher intake of poultry, red meat, animal organ meat, grains (mainly refined), processed meat, fish, soups, leafy and cruciferous vegetables, eggs
He, 2015^13^ | Prudent | Higher intake of dairy products, nuts, eggs, fish, soups, fruits; infrequent intake of processed meat, sugar-sweetened beverages, processed vegetables
He, 2015^13^ | Sweets and seafood | Higher intake of Cantonese desserts, mollusks and shellfish, sugar-sweetened beverages; Lower in grains (mainly refined), leafy and cruciferous vegetables
Hehua, 2021^14^ | Healthy | Higher intake of vegetables, eggs, dairy, whole grains, tubers, legumes and legume products, fruits, fish, and nuts
Hehua, 2021^14^ | Sweet foods | Higher intake of ice cream and candy, cake, fruit and vegetable juices, and sugar-containing beverages
Hehua, 2021^14^ | Animal foods | Higher intake of animal blood, animal organs, preserved eggs, and processed meat products
Hehua, 2021^14^ | Traditional | Higher intake of pickled foods, Chinese sauerkraut, ginger, and garlic
Hu, 2019^17^ | Traditional-TFD | Higher intake of tubers; vegetables; fruits; rice; red meat; eggs; nuts
Hu, 2019^17^ | Sweet foods-TFD | Higher intake of pastries and candies; sweet beverages; shrimps, crabs, and mussels; fruits; red meat
Hu, 2019^17^ | Fried food-beans-TFD | Higher intake of fried foods; beans and products; and dairy products; lower intake of organ meats
Hu, 2019^17^ | Whole grain-seafood-TFD | Higher intake of whole grains; shrimps, crabs, and mussels; nuts; and seaweed; lower intake of eggs; dairy products; and rice
Hu, 2019^17^ | Fish-seafood-FFQ | Higher intake of marine fish; shrimps, crabs, and mussels; freshwater fish; seaweed; organ meat
Hu, 2019^17^ | Protein-sweets-FFQ | Higher intake of dairy products; milk; eggs; beans and products; nuts; pastries and candies
Hu, 2019^17^ | Traditional-FFQ | Higher intake of vegetables; fruits; rice; nuts
Mak, 2018^22^ | Plant-based | Higher intake of green leafy vegetables; cruciferous vegetables; gourd/melon family vegetables; red/orange vegetables; potatoes; root vegetables; bean vegetables; bean products; mushrooms; and fruits; Lower intake of lean pork meat
Mak, 2018^22^ | Meat-based | Higher intake of pork; pig blood curd; ox tripe; organ meat; processed meat; squid; and mushrooms
Mak, 2018^22^ | High protein-low starch | Higher intake of eggs; milk; fish; and lean pork meat; Low intake of noodles; and bread
Miele, 2021^25^ | Obesogenic | Higher intake of ultra-processed and processed foods using NOVA classification (refined carbohydrate; fats; sweets)
Miele, 2021^25^ | Intermediate | Lower intake of same food groups as “Obesogenic” DP
Miele, 2021^25^ | Vegetarian | Higher intake of dairy; fruits; vegetables
Miele, 2021^25^ | Protein | Higher intake of fatty meats; eggs; beans; very low intake of natural foods (using NOVA classification)
Miele, 2021^25^ | Traditional | Higher intake of beans; meats; eggs; natural or minimally processed foods (using NOVA classification)
Pajunen, 2021^26^ | Healthier | Higher intake of vegetables; fruits and berries; rye bread; pasta and rice; fish and seafood; coffee and tea; poultry; margarine and oils; cheeses; and eggs
Pajunen, 2021^26^ | Unhealthier | Higher intake of multigrain and wheat bread; dairy desserts (e.g., ice-cream, whipped cream); sweet pastries; savory pastries; sugar, sweets and chocolate; nuts, seeds, popcorn, potato crisps and dried fruits; beverages; pasta and rice; and poultry
Paknahad, 2019^27^ | High Carbohydrate-Lower Fat | Higher intake of potato; fried potato; flour; egg; cooked carrots; pickles; noodle soup; beans; pomegranate; corn and maize; lentils; low-fat milk; lettuce; and raw carrot
Paknahad, 2019^27^ | High Carbohydrate-Higher Fat | Higher intake of pea; soybean; fish; cabbage; cooked spinach; vegetable; high-fat milk; butter; tomato; cucumber; soup; cooked beans; and diluted yogurt
Paknahad, 2019^27^ | High fiber | Higher intake of cantaloupe; melon; peach; nectarine; green tomatoes; plums; watermelons; pears; apricots
Radesky, 2008^28^ | Prudent | Higher intake of vegetables, fruit, legumes, fish, poultry, eggs, salad dressing, whole grains
Radesky, 2008^28^ | Western | Higher intake of red and processed meats, sugar-sweetened beverages, French fries, high-fat dairy products, desserts, butter, refined grains
Tryggvadottir, 2016^32^ | Prudent | Higher intake of seafood, eggs, vegetables, fruit and berries, vegetable oils, nuts and seeds, pasta, breakfast cereals, and coffee and tea; lower intake of soft drinks and French fries
Yong, 2020^35^ | DP 1 | Higher intake of green leafy vegetables; other vegetables; nuts, seeds and legumes; fruits; eggs; milk and dairy products
Yong, 2020^35^ | DP 3 | Higher intake of rice, noodles, and pasta; oils and fats; high energy beverages; fish and seafood; sweet foods; poultry and meat
Yong, 2020^35^ | DP 4 | Higher intake of green leafy vegetables; other vegetables; nuts, seeds, and legumes; fruits
Yong, 2020^35^ | DP 6 | Higher intake of eggs; milk and dairy products; rice, noodles, and pasta; high energy beverages; fish and seafood; sweet foods; poultry and meat; bread, cereal, and cereal products; processed meat
Zhou, 2018^36^ | Beans-vegetables | Higher intake of root vegetables; mushrooms and algae; melon and solanaceous vegetables; beans and bean products (soybean, mung bean, soybean milk, bean curd, etc.); leafy and cruciferous vegetables
Zhou, 2018^36^ | Nuts-whole grains | Higher intake of nuts; whole grains, dairy products
Zhou, 2018^36^ | Organ-poultry-seafood | Higher intake of animal organ and blood; seafood; poultry
Zhou, 2018^36^ | Fish-meat-eggs | Higher intake of red meat; freshwater fish; eggs
Zhou, 2018^36^ | Rice-wheat-fruits | Higher intake of rice and wheat products; fruits

### Timing of exposure assessment

A third of articles assessed diet once during the first trimester of pregnancy (<14 GW)^2,^ ^4,^ ^5,^ ^11,^ ^16,^ ^21,^ ^23,^ ^24,^ ^26,^ ^27,^ ^29,^ ^31,^ ^34^ and another third of articles assessed diet once after 14 GW, but before a GDM diagnosis (24-28 GW).^3,^ ^6,^ ^8–10,^ ^13,^ ^15,^ ^22,^ ^25,^ ^32,^ ^33,^ ^36,^ ^43^ One article measured diet once between 13 and 16 GW,^1^ while another measured diet once between 8 and 16 GW,^12^ and a third measured diet once between 5 and 25.6 GW.^28^ A final third of articles measured diet multiple times during pregnancy, usually during the first and/or second trimester and again before outcome assessment,^7,^ ^14,^ ^17,^ ^19,^ ^20,^ ^30,^ ^35,^ ^37–42,^ ^44,^ ^45^ One article did not report the specific timing of dietary assessment.^18^

### Outcome

#### Gestational Diabetes Mellitus

Thirty-seven articles^2,^ ^3,^ ^5–7,^ ^10–19,^ ^21–29,^ ^31–38,^ ^40,^ ^41,^ ^43–45^ reported GDM as an outcome.

About half of articles reported >10% GDM incidence^2,^ ^5,^ ^10,^ ^13,^ ^14,^ ^16–18,^ ^22,^ ^24,^ ^26,^ ^31,^ ^32,^ ^35,^ ^37,^ ^38,^ ^40,^ ^41,^ ^44,^ ^45^; of those, another half reported >20% GDM incidence.^2,^ ^5,^ ^10,^ ^14,^ ^17,^ ^18,^ ^24,^ ^26,^ ^37,^ ^38^ Another article had high incidence of dysglycemia, but the authors did not report specifically on GDM incidence.^30^ Four additional articles reported GDM incidence ~8-9%^7,^ ^15,^ ^33,^ ^36^ and the remaining articles reported <8% GDM incidence.^3,^ ^4,^ ^6,^ ^11,^ ^19–21,^ ^23,^ ^25,^ ^27,^ ^28,^ ^43^ or did not report GDM incidence.^1,^ ^8,^ ^9,^ ^12,^ ^29,^ ^34^

#### Fasting Blood Glucose

Nine articles reported fasting blood glucose (FBG) levels that were not part of oral glucose tolerance test (OGTT) results.^1,^ ^4,^ ^8,^ ^38,^ ^39,^ ^41–44^ One article reported FBG in the second trimester only,^1^ and 5 articles reported FBG in the third trimester only.^8,^ ^38,^ ^39,^ ^41,^ ^44^ Three articles reported FBG multiple times during pregnancy, including the first and second trimester,^42^ and the second and third trimester.^4,^ ^43^

#### Glucose Tolerance/Insulin Resistance

Six articles reported values from an OGTT (fasting, 1h, 2h, and/or 3h blood glucose) conducted between 24 and 28 GW results.^17,^ ^21,^ ^24,^ ^38,^ ^39,^ ^41^ An additional article reported risk of impaired glucose tolerance, defined as failed non-fasting, 50g OGTT and ≤1 abnormal result on a 100g OGTT between 26 and 28 GW.^29^ Eight articles reported insulin resistance results calculated using HOMA-IR.^4,^ ^9,^ ^20,^ ^38,^ ^39,^ ^41,^ ^43,^ ^44^ Six articles reported insulin resistance in both the second and third trimesters,^4,^ ^38,^ ^39,^ ^41,^ ^43,^ ^44^ while 2 articles reported insulin resistance in the third trimester only.^9,^ ^20^

#### HbA1C

Five articles reported hemoglobin A1C (HbA1C) measures,^7,^ ^38,^ ^39,^ ^41,^ ^44^ 4 articles reported HbA1C in both the second and third trimesters,^38,^ ^39,^ ^41,^ ^44^ and 1 article reported HbA1C in the second trimester only.^38^

#### Other

One article reported risk of dysglycemia at 24-28 GW, which was defined as an abnormal 50g glucose challenge; abnormal value on 100g OGTT (≥1): fasting ≥95, 1h ≥180, 2h ≥155, 3h ≥140 mg/dL; or a clinical diagnosis of GDM.^30^

## Synthesis of the evidence

Twenty-four dietary patterns from 23 articles (17 unique trials or cohorts) were associated with lower risk of GDM.^1,^ ^2,^ ^6,^ ^13,^ ^14,^ ^17–19,^ ^21–24,^ ^26,^ ^31–33,^ ^36–39,^ ^41,^ ^44,^ ^45^ Although there was variation in the foods and food groups represented in the dietary patterns, there was somewhat consistent evidence that these dietary patterns were characterized by higher intakes of vegetables, fruits, nuts and seeds, whole grains, legumes, fish/seafood, and unsaturated fats; as well as lower intakes of red and processed meat, added sugars, and saturated fats.

Ten dietary patterns from 8 articles were associated with higher risk of GDM.^1,^ ^7,^ ^10,^ ^13,^ ^16,^ ^17,^ ^27,^ ^36^ These dietary patterns tended to be less aligned with the intakes of food groups mentioned above, including higher intakes of red and processed meat and added sugars, and both higher and lower intakes of grains, dairy, and vegetables. Thus, this evidence does not contradict the results of dietary patterns with beneficial GDM associations. It is also important to note that no RCT or NRCT demonstrated a detrimental effect on any outcomes.

Fifty-one dietary patterns from 30 articles (26 unique trials or cohorts) showed no statistically significant association with any outcomes.^3–5,^ ^7–15,^ ^17,^ ^19,^ ^20,^ ^22,^ ^25–31,^ ^33–36,^ ^40,^ ^42,^ ^43^ However, the results tended to be in the same direction as the statistically significant results: dietary patterns characterized by higher intakes of vegetables, fruits, nuts and seeds, whole grains, legumes, fish/seafood, and unsaturated fats; as well as lower intakes of red and processed meat, added sugars, and saturated fats generally suggested a beneficial association, and dietary patterns that were less aligned with those foods/groups generally suggested a detrimental association.

A summary of the findings is below. Please refer to Table 7 for more details and Appendix 6 for a visualization of the dietary pattern components.

### Intervention studies

Five trials that reported a beneficial effect on risk of GDM implemented a Mediterranean-style diet intervention that was generally characterized by higher intakes of vegetables, fruit, legumes, white meat over red meat, fish or shellfish, nuts, olive oil, and a traditional sauce of tomatoes, garlic, onion, or leeks sauteed in olive oil; and lower intakes of red and processed meat, sugar-sweetened beverages (SSB) and commercial sweets, and saturated fats.^37–39,^ ^41,^ ^44^

The multicenter, U.K.-based ESTEEM RCT randomized participants with metabolic risk factors to a Mediterranean-style diet supplemented with mixed nuts and extra virgin olive oil (EVOO) (provided by investigators) or usual care.^37^ The intervention reduced risk of GDM compared to usual care in all metabolically at-risk participants and participants with BMI ≥30. There was no effect among participants with BMI <30 kg/m^2^, participants with normal and elevated triglycerides, and participants with or without chronic hypertension.

The St. Carlos GDM Prevention Study RCT conducted in Spain also included a Mediterranean-style diet supplemented with nuts and EVOO (provided by investigators) intervention, which was compared to a Mediterranean-style diet with restricted fat (i.e., lower Mediterranean diet alignment).^38^ The intervention reduced risk of both overall GDM and insulin-treated GDM, as well as lowered fasting blood glucose and HbA1C at both 24-28 GW and 36-38 GW, OGTT 2h blood glucose, and insulin resistance values at 24-28 GW.

The intervention did not have an effect on OGTT 1h blood glucose or insulin resistance values at 36-38 GW. A secondary analysis of the St. Carlos GDM Prevention Study that restricted the analysis to normoglycemic participants^39^ found that the intervention lowered fasting blood glucose and HbA1C at both 24-28 GW and 36-38 GW compared to the control, but had no statistically significant effect on OGTT 1h or 2h blood glucose or insulin resistance values at either 24-28 GW or 36-38 GW. The similar, but less pronounced, results compared to the original trial may be explained by the exclusion of participants who ultimately developed GDM, which would expectedly result in smaller differences between groups. Another secondary analysis of the St. Carlos GDM Prevention Study only included Hispanic participants and found that the intervention reduced risk of GDM and high HbA1C compared to the control. None of the OGTT comparisons were statistically significantly different. The intervention lowered fasting blood glucose at 36-38 GW and insulin resistance values at 24-28 GW and the relationship between the intervention and insulin resistance values at 36-38 GW neared significance.^41^ Additionally, Melero et al.^41^ compared outcomes in Hispanic participants from a non-randomized group, where the intervention was implemented in a “real world” setting, to the original trial control group. In this “real world” group, participants were recommended to consume EVOO and nuts, but were not provided with these foods. The “real world” intervention also reduced risk of GDM and high HbA1C compared to the control group in the trial setting. OGTT results were mixed. The “real world” intervention did not have an effect on fasting blood glucose at 36-38 GW or insulin resistance values at either follow-up.

Zhao et al. conducted an RCT that examined a Mediterranean-style diet intervention in China.^44^ The intervention group was also encouraged to consume EVOO and roasted pistachios every day (but was not supplied with EVOO or nuts), while the control group was recommended to restrict dietary fat. The intervention reduced risk of GDM, as well as lowered fasting blood glucose and HbA1C at both 24-28 GW and 36-38 GW but did not have an effect on insulin resistance values at 24-28 GW or 36-38 GW.

Three additional trials reported no statistically significant effects on risk of GDM.^40,^ ^42,^ ^43^

A hospital-based RCT in Greece investigated the effect of software that delivered personalized dietary plans based on the Mediterranean Diet, paired with standard care recommendations in line with the “National Dietary Guidelines for Pregnancy”. ^42^ The control group also received standard care recommendations. The intervention reduced fasting blood glucose from baseline to follow-up in the intervention group but did not have a statistically significant effect over time compared to standard care. However, this RCT had a sample size of 40 participants, was not directly designed to examine the relationship between DP and GDM, and showed that adherence to the Mediterranean Diet was already higher in the intervention group at baseline, potentially limiting the ability to detect intervention effects.

In the U.S.-based MOMFIT RCT,^43^ participants with pre-pregnancy BMI ≥25 kg/m^2^ were randomized to a calorie-controlled, DASH-style diet and lifestyle intervention or usual care. Modifications to a typical DASH diet included recommendations to avoid fish considered higher in mercury and include calcium-rich, vitamin D-enriched dairy or calcium-fortified non-dairy products. The intervention had no effect on fasting blood glucose or insulin resistance values at 35 GW. However, the trial was not designed to investigate GDM; the primary outcome was gestational weight gain.

The OPTIMISE RCT was conducted in Australia^40^ where participants were randomized to a lifestyle intervention including dietary advice consistent with the Australian dietary standards or standard care. Participants in the intervention group were specifically advised to increase their intake of fiber, consume 2 servings of fruit per day, 5 servings of vegetables per day, and three servings of dairy per day. The intervention did not affect the risk of GDM, although the Healthy Eating Index scores were marginally different (by about 2 points) between groups at both follow-up points, which may indicate a deviation from the intended intervention. Diagnostic criteria for GDM also changed during the course of the trial and there was no indication of how many participants from each group were diagnosed using either criterion.

### Observational studies

#### Studies that suggest an association between dietary patterns and lower risk of GDM

Dietary patterns based on the following indices/scores were statistically significantly associated with lower risk of GDM: the Mediterranean Diet Score and its variations,^2,^ ^18,^ ^23,^ ^31^ Healthy Eating Indices,^19,^ ^21,^ ^32^ Chinese Dietary Guidelines Compliance Index for Pregnant Women (CDGCI-PW),^6^ Healthy Food Intake Index,^24^ Plant-based Diet Index and healthy Plant-based Diet Index,^33^ and a lower nutrition risk score.^45^ Dietary patterns based on the following indices/scores suggested a beneficial association with risk of GDM, despite a lack of statistically significant results: Mediterranean Diet Score and its variations,^8,^ ^9,^ ^19,^ ^20,^ ^31^ Healthy Eating Indices,^3,^ ^29,^ ^30,^ ^34^ and DASH.^19^ These beneficial patterns were generally characterized by higher intakes of vegetables, fruits, whole grains, legumes, fish and seafood, nuts and seeds, and unsaturated fats; and lower intakes of red and processed meat and added sugars.

The following dietary patterns derived via factor or cluster analysis were statistically significantly associated with lower risk of GDM: ‘Vegetable’ pattern,^13^ ‘Prudent’ pattern,^32^ ‘Vegetable-fruits & protein’ pattern,^1^ ‘Healthy’ pattern,^14^ two variations of a ‘Traditional’ pattern,^17^ ‘High protein-low starch’ pattern,^22^ ‘Healthier’ pattern,^26^ and a ‘Rice-wheat-fruits’ pattern.^36^ The following dietary patterns derived via factor or cluster analysis suggested a beneficial association with risk of GDM, despite a lack of statistically significant results: ‘Plant-based’ pattern, ^22^ two variations of a ‘Prudent, Healthy’ pattern, ^35^ and a ‘Prudent’ pattern.^7^ These beneficial patterns were generally characterized by higher intakes of vegetables, fruits, grains, eggs, and nuts and seeds. Results and methods of interest from these articles are included below and in Table 7.

Eight articles generally found a stronger association between DP and risk of GDM among participants at higher risk compared to participants at lower risk for GDM,^2,^ ^13,^ ^17,^ ^22,^ ^24,^ ^26,^ ^32,^ ^45^ including those with higher pre-pregnancy BMI^2,^ ^22,^ ^26,^ ^32,^ ^45^, who were ≥35y,^2,^ ^17,^ ^45^ or with a family history of diabetes mellitus.^13^ A hospital-based study conducted in Iceland^32^ found that greater alignment with the Icelandic Healthy Eating Index was associated with lower GDM diagnosis rate among participants with pre-pregnancy BMI ≥25 kg/m^2^.^32^ This study also examined a factor analysis-derived ‘Prudent’ pattern in relation to GDM and found that greater alignment was associated with lower risk of GDM among all participants and participants with pre-pregnancy BMI ≥25 kg/m^2^. A secondary analysis of the control arm participants from the Finnish RADIEL trial,^24^ which recruited participants at high risk for GDM, found that greater alignment with the Healthy Food Intake Index trended toward a lower risk of GDM, but did not reach statistical significance. Greater alignment with Healthy Food Intake Index was inversely associated with 75g OGTT fasting blood glucose and 2h blood glucose measures, but was not associated with 75g OGTT 1h blood glucose, although the sample size for this study was relatively small (n=137.In a secondary analysis from the St. Carlos GDM Prevention Study,^2^ greater alignment with the modified Mediterranean Diet Adherence Screener was associated with reduced risk of GDM among participants with pre-pregnancy BMI ≥25 kg/m^2^ and those who were primiparous. High alignment, but not moderate alignment, was associated with reduced risk of GDM among participants ≥35y when compared to low alignment; results among participants <35y were less clear. There was no association between the modified Mediterranean Diet Adherence Screener and risk of GDM among participants with pre-pregnancy BMI <25 kg/m^2^ or who were multiparous. In an analysis of the China-based Born in Guangzhou Cohort Study (BIGCS) cohort,^13^ greater alignment with the ‘Vegetable’ DP was associated with a lower risk of GDM among all participants and those with a family history of diabetes, but not among those with no family history of diabetes. In another China-based article from the Born in Shenyang Cohort Study (BISCS), greater alignment with the ‘Traditional’ pattern derived from either 3d food diaries or a food frequency questionnaire was associated with a lower risk of GDM among all participants and participants ≥35y, but not among participants <35y. Greater alignment with the ‘High protein-low starch’ pattern derived in a third article conducted in China^22^ was associated with lower risk of GDM among participants with pre-pregnancy BMI ≥24 kg/m^2^, but there was no association among all participants. Additionally, there was no effect modification by age or family history of diabetes. An article from Finland^26^ found that among participants with pre-pregnancy BMI ≥25 kg/m^2^, alignment with the fourth quintile of the ‘Healthier’ pattern was associated with a reduced risk of GDM compared to the first quintile of the ‘Healthier’ pattern. All other associations were statistically non-significant but were in the same direction as the statistically significant associations. A Spanish hospital-based study examined nutrition risk factors in relation to risk of GDM.^45^ Having no nutrition risk factors compared to four nutrition risk factors was associated with reduced risk of GDM in participants with pre-pregnancy BMI ≥25 kg/m^2^, <35y, and who were primiparous. Having no nutrition risk factors compared to four nutrition risk factors was not associated with risk of GDM in participants with pre-pregnancy BMI <25 kg/m^2^, ≥35y, or who were multiparous, but results were in a beneficial direction.

Three articles found statistically significant results among participants with moderate, but not high, alignment with a dietary pattern compared to low alignment.^14,^ ^19,^ ^36^ Li et al. analyzed results from the NICHD Fetal Growth Studies–Singletons cohort.^19^ Moderate alignment, but not high alignment, with the Alternative Healthy Eating Index in the first trimester was associated with reduced risk of GDM when compared to low alignment. Greater alignment with the Alternative Healthy Eating Index during the second trimester was associated with reduced risk of GDM. In the analysis of the NEC-Biobank Chinese cohort,^14^ the third quartile of the ‘Healthy’ pattern was associated with reduced risk of GDM compared to the first quartile. All other associations were statistically non-significant but were in the same direction as the statistically significant association. Lastly, one analysis from the Tongji Maternal and Child Health Cohort (MCHC)^36^ found that the third quartile of alignment with the ‘Rice-wheat-fruits’ pattern compared to the first quartile (and per SD increase; p for trend) was associated with a reduced risk of GDM in all participants; participants with pre-pregnancy BMI 18.5-23.9 kg/m^2^; and participants with no family history of diabetes. Results for participants with pre-pregnancy BMI <18.5 kg/m^2^ were only statistically significant for continuous alignment with the ‘Rice-wheat-fruits’ pattern. There was no statistically significant association among participants with pre-pregnancy BMI ≥24 kg/m^2^ or participants with a family history of diabetes. Results for participants with pre-pregnancy BMI ≥24 kg/m^2^ were in a similar direction, despite the lack of statistical significance.

Thirteen articles reported dietary patterns that were not statistically significantly associated with any GDM outcome.^3,^ ^7–10,^ ^15,^ ^19,^ ^20,^ ^22,^ ^27,^ ^29–31,^ ^34,^ ^35^. Although the results did not reach statistical significance, the findings tended to be in the same beneficial direction. In addition, some of the statistically non-significant results may be explained by study methods, such as smaller sample sizes,^8,^ ^9,^ ^15,^ ^20^ post-exposure interventions that may have occurred after a GDM diagnosis that could have affected outcomes later in pregnancy,^8,^ ^9,^ ^20^ and/or non-standard dietary assessment methods.^30^

Three articles reported statistically non-significant results that tended to be in the opposite direction as statistically significant results, meaning that dietary patterns commonly considered “detrimental” suggested a beneficial association with risk of GDM,^5,^ ^28,^ ^33^ Some of the results may be explained by study methods, such as non-standard GDM assessment methods.^5^ Additionally, in the analysis of the China-based Tongji Maternal and Child Health Cohort (MCHC),^33^ healthy plant-based foods were grouped with animal-based foods as negative components in this unhealthy Plant-based Diet Index, which may have affected the relationship between the dietary pattern and risk of GDM.

#### Studies that suggest an association between dietary patterns and higher risk of GDM

Dietary patterns based on the following indices/scores were statistically significantly associated with a higher risk of GDM: dietary risk score.^16^ This detrimental dietary pattern was characterized by higher intakes of processed meat and SSB/artificially sweetened beverages and sweets; and lower intakes of whole grains, dairy, and vitamin D. The following dietary patterns derived via factor or cluster analysis were associated with higher risk of GDM: ‘Sweet and seafood’ pattern,^13^ ‘Western’ and ‘Traditional’ patterns,^7^ ‘High fat-fast food’ pattern,^1^ ‘African/Caribbean’ and ‘Processed’ patterns,^10^ ‘Whole grain-seafood’ pattern,^17^ ‘High Carbohydrate-Lower fat’ pattern,^27^ and a ‘Fish-meat-eggs’ pattern.^36^ The following dietary patterns derived via factor or cluster analysis suggested a detrimental association with risk of GDM, despite a lack of statistically significant results: ‘High Carbohydrate-Higher Fat’ pattern, ^27^ ‘Snacks’ pattern, ^10^ ‘Meat-based’ pattern, ^22^ ‘Western’ pattern, ^35^ and a ‘Mixed’ pattern compared to a ‘Prudent’ pattern.^7^ These detrimental dietary patterns were generally characterized by higher intakes of fish/seafood, red and processed meat, and added sugars, with mixed intakes of vegetables, grains, and dairy. Results and methods of interest from these articles are included below.

Three articles generally found a stronger statistically significant association between DP and risk of GDM among participants at higher risk compared to participants at lower risk,^10,^ ^16,^ ^36^ including those with higher pre-pregnancy BMI, ^10,^ ^16,^ ^36^ and with a family history of diabetes mellitus. ^36^ In an article from the PREgnant Women of ICEland (PREWICE) cohort study,^16^ greater alignment with a dietary risk score was associated with higher risk of GDM among all participants and participants with pre-pregnancy BMI ≥25 kg/m^2^, but not among participants with pre-pregnancy BMI<25 kg/m^2^. A secondary analysis of the UPBEAT trial in the U.K.,^10^ which exclusively recruited participants with pre-pregnancy BMI ≥30 kg/m^2^, found that greater alignment with the ‘African/Caribbean’ DP and ‘Processed’ DP was associated with higher risk of GDM. Lastly, an article from the Tongji MCHC^36^ reported that greater alignment with the ‘Fish-meat-eggs’ pattern was associated with a greater risk of GDM in all participants; participants with pre-pregnancy BMI 18.5-23.9 kg/m^2^ and ≥24 kg/m^2^; and participants with (association slightly attenuated) and without a family history of diabetes mellitus, but not among participants with pre-pregnancy BMI <18.5 kg/m^2^.

Two articles conducted analyses where the comparator was another dietary pattern. ^7,^ ^27^ Alignment with the ‘High Carbohydrate-Lower Fat’, but not the ‘High-Carbohydrate-Higher fat’, pattern was associated with greater risk of GDM when compared to alignment with the ‘High fiber’ pattern in an article from Iran.^27^ Although the ‘High Carbohydrate-Higher fat’ pattern results did not reach statistical significance, they suggested a detrimental association. Alignment with the ‘Western’ and ‘Traditional’ patterns, compared to alignment with the Prudent pattern, was found to be associated with greater risk of GDM and greater risk of high HbA1C in a China-based article.^7^ Although results did not reach statistical significance, alignment with the ‘Mixed’ pattern suggested a detrimental association with risk of GDM and risk of HbA1C, compared to alignment with the ‘Prudent’ pattern. This article also reported results from analyses where the comparator was different alignment with the same pattern: moderate, but not high, alignment with the ‘Western’ DP was associated with greater risk of GDM, and greater alignment with the ‘Traditional’ DP was associated with greater risk of GDM.

Lastly, the highest, but not middle, tertile of alignment with a ‘Sweets and seafood’ pattern was statistically significantly associated with higher risk of GDM in an article from the BIGCS cohort study in China.^13^ The diet assessment was administered late at 24-27 GW and the GDM assessment timing was not reported, although the authors state that it was a prospective study.

Five articles reported statistically non-significant results that tended to be in the opposite direction as statistically significant results, meaning that dietary patterns commonly considered “beneficial” suggested a detrimental association with risk of GDM.^4,^ ^5,^ ^10,^ ^11,^ ^14,^ ^28,^ ^33^ However, some of the results may be explained by study methods, such as smaller sample sizes,^4^ post-exposure interventions that may have occurred after a GDM diagnosis that could have affected outcomes later in pregnancy,^4^ non-standard GDM assessment methods,^5^ and up to two dietary assessments administered after a GDM diagnosis.^14^

#### Studies that report unclear statistically non-significant findings

Fifteen articles reported statistically non-significant results that indicated a null association^10,^ ^11,^ ^13,^ ^15,^ ^25,^ ^29,^ ^36^ or that were unclear^7,^ ^12–14,^ ^17,^ ^22,^ ^25,^ ^26,^ ^28,^ ^35,^ ^36^ due to analyses where one dietary pattern was compared to another dietary pattern,^25^ dietary patterns with combinations of foods that were difficult to interpret,^7,^ ^12–14,^ ^17,^ ^22,^ ^26,^ ^35,^ ^36^, and/or reported results by quantiles did not show a suggested trend in direction.^14,^ ^17,^ ^22,^ ^26,^ ^28,^ ^36^

## Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between dietary patterns consumed during pregnancy and risk of gestational diabetes mellitus?” based on their review of the body of evidence. (see Table 6)

Dietary patterns consumed during pregnancy that are characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, whole grains, fish/seafood, and unsaturated fats, and lower intakes of red and processed meat, added sugars, and saturated fats are associated with lower risk of gestational diabetes mellitus. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

Table 6 Conclusion statement, grade for dietary patterns consumed during pregnancy and risk of gestational diabetes mellitus

Conclusion Statement | Dietary patterns consumed during pregnancy that are characterized by higher intakes of vegetables, fruits, legumes, nuts and seeds, whole grains, fish/seafood, and unsaturated fats, and lower intakes of red and processed meat, added sugars, and saturated fats are associated with lower risk of gestational diabetes mellitus. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 45 articles: 28 prospective cohort studies, 6 randomized controlled trials, 1 non-randomized controlled trial, 1 retrospective cohort study
Consistency | Results were somewhat consistent in direction and magnitude of effect across significant and non-significant results. Some of the inconsistencies could be explained by methodological differences.
Precision | Results were limited in precision, with a small number of studies demonstrating sufficient power, as well as wide variance around the effect estimates.
Risk of bias | Most studies had overall high risk of bias due to confounding, deviations from intended interventions, post-exposure interventions, exposure assessment methods, selection bias, missing data, and selective reporting of the results.
Directness | Majority of studies were designed to directly examine the relationship between dietary patterns and gestational diabetes mellitus.
Generalizability | Limited generalizability to the U.S. population when considering country, SEP, and DPs studied. Among studies in the U.S. and U.K., there was some racial and ethnic diversity.

### Assessment of the evidence

The body of evidence included 45 articles from 28 PCS, 6 RCT, 1 NRCT, and 1 RCS (see Table 6). The body of evidence included some limitations that are specific to the challenges of conducting research in pregnant populations. For example, diet assessments during early pregnancy can be affected by the timely awareness of pregnancy and by variation in diet related to nausea and vomiting of pregnancy. Additionally, due to the finite length of pregnancy, there is a relatively short time between the dietary intake assessment and the outcome assessment, particularly for GDM, which is usually assessed mid-pregnancy. The association of dietary patterns with GDM may also be different depending on the severity of GDM, but only 1 article reported insulin-treated GDM results separately from overall GDM results. Finally, there was wide variation in dietary patterns studied and consistency across the dietary patterns was sometimes limited.

Publication bias is always a concern and is a risk in this systematic review because the search did not include the gray literature. However, this body of evidence includes articles with both large and small sample sizes, as well as statistically significant and null findings, so publication bias may be less likely.

#### Consistency

There was moderate consistency in direction and magnitude of effect across statistically significant and non-significant results. Most trials examined a Mediterranean-style diet, and thus there was little variation in the individual foods and food groups consumed. Some of the inconsistencies in statistically non-significant findings could be explained by methodological differences, such as small sample sizes, lack of trials being designed to assess the relationship between dietary patterns and risk of GDM, and deviations from the intended interventions.

There was some consistency in the direction of effect across statistically significant and non-significant results in observational study articles. However, there was wide variation in the magnitude of effect and composition of the dietary patterns (see Synthesis of the Evidence); few of the inconsistencies in findings could be explained by methodological differences.

#### Precision

There were a small number of intervention study articles included in the body of evidence. Results had wide confidence intervals and less than half of the intervention study articles reported a sufficient sample size for a GDM outcome. One trial did not report a power analysis, 1 reported an insufficient sample size for detecting a difference in gestational weight gain, and 3 reported a sufficient sample size for a non-GDM outcome.

There was a larger pool of cohort studies than intervention studies, but very few demonstrated sufficient power and there were concerns about wide variances around the effect estimates.

#### Risk of bias

Half of intervention study articles had overall high risk of bias due to concerns about deviations from intended interventions and selective reporting of the results. For deviations from intended interventions, issues arose when more participants in one group were diagnosed with GDM, and the trial also reported post-GDM diagnosis outcomes. If participants diagnosed with GDM were treated with diet or insulin and GDM rates differed between the intervention and control group, this could have affected the results later in pregnancy. There were also concerns about selective reporting of results when there was no pre-specified analysis plan, there were more analyses listed in the protocol than what was reported in the article, or when there was not strong justification for secondary analyses that were not specified in the original protocol and that only included a subset of participants. Risk of bias domain ratings for intervention study articles can be found in Table 8 and Table 9.

Most observational study articles had overall high risk of bias due to concerns about confounding, exposure assessment methods, selection bias, missing data, and selective reporting of the results. There were only a handful of observational studies that controlled for all key confounders while also not controlling for any post-exposure variables (e.g., gestational weight gain). Issues arose for bias due to exposure assessment methods when the diet assessment was not stated to have been validated in a pregnant population, if diet was assessed very close to the time of GDM diagnosis, and/or if the measured exposure did not well characterize a dietary pattern (i.e., only including a few food groups). Selection bias was suspected if participants were excluded from the study or analysis based on characteristics that were observed after the start of the exposure that were likely to have been influenced by both the exposure and the outcome. Some articles also did not report adequate information on missing data, or when they reported missing data, they did not perform analyses to prove the results were not biased by missing data. Concerns about selection of the reported result resulted from lack of a pre-specified analysis plan, or when there was clear or suspected selective reporting based on the desirability of the magnitude (or statistical significance) of results. Risk of bias domain ratings for observational study articles can be found in Table 10.

#### Directness

Half of the trials were directly designed to examine the relationship between dietary patterns and a GDM outcome. Of the trials that were not directly designed to examine that relationship, 1 was designed to investigate the effect of a lifestyle intervention on gestational weight gain, 1 excluded participants who developed GDM, 1 examined the effect of a dietary plan software system, and 1 looked at the impact of diet and exercise combined (although physical activity did not differ between groups).

All the observational studies were designed to look at the relationship specified in the review question. Of these, 9 were a secondary analysis of a trial or cohort that was not originally designed to investigate the relationship between a dietary pattern and a GDM outcomes (e.g., a trial investigating the effect of fish oil and/or probiotic supplementation)

#### Generalizability

Only 1 trial was conducted in the U.S. and most trials reported that the majority of participants were employed, had at least “middle” class income, and or had pre-pregnancy normal weight. When reported, there was a mix of race and/or ethnicity and education level of participants across intervention study articles.

Ten articles from 6 unique cohorts were conducted in the U.S. There were many observational study articles that did not report race and/or ethnicity, but of the ones that did, there was some diversity, especially in the articles from the U.S. and U.K. However, no articles reported American Indian or Alaska Native participants and there was limited generalizability when considering SEP, pre-pregnancy BMI, and dietary patterns represented. In the articles that conducted subgroup analyses by pre-pregnancy BMI, there was a stronger relationship seen for participants with pre-pregnancy BMI ≥25 kg/m^2^ compared to the relationship seen for participants with pre-pregnancy BMI <25 kg/m^2^.