# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by a data visualization table (Table A 14) that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence. During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components in the dietary patterns studied along with the direction, magnitude, and statistical significance of reported results. Detailed information about the body of evidence, including a description of each dietary pattern in more detail, study and population characteristics, outcomes, key confounders accounted for, and funding sources, are summarized in the evidence tables of this report (Table 5 and Table 7).

Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. Two additional columns, “Other, A” and “Other, B”, captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast food, ready-to-eat dishes, pizza, and chocolate. Multiple symbols in each cell mean that the dietary pattern included multiple components from that column/category. Empty cells mean that the dietary pattern did not include a component within that column/category.

Table A 14 Visualization of dietary pattern components organized by approach across evidence examining the relationship between dietary patterns consumed during pregnancy and gestational diabetes mellitus^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. ^†^ † Abbreviations: AF, animal fat; AN, animal food groups; AS, added sugar; C, coffee; CH, cheese; F, fish; FF, fried potato; FP, fatty and processed meat; Fr, included with Fruit component; FVJ, fruit and vegetable juices; G, grains or cereals; HPL, healthy plant-based food; JSD, juice and/or sweetened drinks; LN, legumes and nuts; MUFA, monounsaturated fatty acids; M, meat and/or meat products; N, nuts; n-3, omega-3 fatty acids; OC, oils and condiments; OF, oils and fats; OO, olive oil; P, processed meat; PL, plant food groups; PRO, protein; PUFA, polyunsaturated fatty acids; R, red meat; RP, red and processed meat; RW, red and white meat; S, seafood; SD, salad dressing; SFA, saturated fatty acids; T, tea; TFA, trans fatty acids; UP, ultra-processed foods; UPL, unhealthy plant-based food; W:R, ratio of white to red meat; Y, yogurt

Article; Dietary pattern | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish, Seafood | Meats (Red Processed) | Lean meats (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | SSB | Sugary Foods | Fat: Unsaturated, Oils | Fat: Other | Fat: Saturated | Alcohol | Sodium | Tea and Coffee | Other A | Other B
RCT
Al Wattar, 2019;^37^ Mediterranean (Med.) w/ mixed nuts + EVOO | ▲ | | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼
Assaf-Balut, 2017;^38^ Med. w/ mixed nuts + EVOO | ▲ | | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | ▲ | | | ▲
Assaf-Balut, 2019;^39^ Med. w/ mixed nuts + EVOO | ▲ | | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | ▲ | | | ▲
Melero, 2020;^41^ Med. w/ mixed nuts + EVOO | ▲ | | ▲ | | | ▲ N | | | | ▲ F | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | | | | ▲
Zhao, 2022;^44^ Med. w/ recommended pistachios + EVOO | ▲ | | ▲ | ▲ | Fr | ▲ N | | | | ▲ | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | ▲ | | | ▲
Dodd, 2019;^40^ Australian dietary standards | ▲ | | | ▲ | | | | | | | | | | ▲
Papandreou, 2023;^42^ Med. personalized dietary plan | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ F | ▼ RP | ▼ | | | | ▼ | | | | | | ▼
Van Horn, 2018;^43^ Calorie-controlled, DASH-type diet | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
NRCT
Melero, 2020;^41^ Med. w/ mixed nuts + EVOO | ▲ | | ▲ | | | ▲ N | | | | ▲ F | ▼ RP | ▲ W:R | | | | | ▼ | ▼ | ▲ OO | | ▼ | | | | ▲
Index/Score
Assaf-Balut, 2018;^2^ Modified MEDAS | ▲ | | | ▲ | ▼ | ▲ N | | | | | | | | | | | | | ▲ OO
Flor-Alemany, 2021;^8^ MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ F | ▼ RP | ▼ | | | | ▼ | | | ▲ OO
Flor-Alemany, 2022;^9^ MedDietScore | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ F | ▼ RP | ▼ | | | | ▼ | | | ▲ OO
Karamanos, 2014;^18^ Med. Diet Indices | ▲ | ▲ | ▲ | ▲ | | | | ▲ | | ▲ F | ▼ M | M | ▼ | ▼ | | | | | ▲ OO:AF | | OO:AF
Li, 2021;^19^ aMED | ▲ | | | ▲ | | ▲ N | | ◄ | | ▲ F | ▼ RP | ▲ | | ◄ | | | | | | | | | ▼
Lindsay, 2020;^20^ MDS | ▲ | | ▲ | ▲ | | ▲ N | | ▲ | | ▲ F | ▼ RP | | | ▼ | | | | | ▲ MUFA: SFA | | MUFA: SFA
Makarem, 2022;^23^ aMED | ▲ | | ▲ | ▲ | | ▲ N | ▲ | | | ▲ F | ▼ RP | | | | | | | | ▲ MUFA: SFA | | MUFA: SFA | ◄
Tranidou, 2023;^31^ MDS | ▲ | | ▲ | ▲ | | ▲ N | | ▲ | | ▲ F | ▼ RP | | | ▼ | | | | | ▲ MUFA: SFA | | MUFA: SFA | ◄
Tranidou, 2023;^31^ Modified MDS | ▲ | | ▲ LN | ▲ | | LN | ▲ | | | ▲ | ▼ FP | ▲ | | | ▲ | ▼ | ▼ | ▼ | ▲
Badon, 2017;^3^ AHEI-2010 | ▲ | | ▲ LN | ▲ | ▼ | LN | ▲ | | | | ▼ RP | | | | | | ▼ | | ▲ n-3; PUFA | ▼ TFA
Bernier, 2023;^4^ AHEI-2010 | ▲ | | ▲ LN | ▲ | ▼ | LN | ▲ | | | | ▼ RP | | | | | | ▼ | | ▲ n-3; PUFA | ▼ TFA
Li, 2021;^19^ AHEI-2010 | ▲ | | ▲ LN | ▲ | ▼ | LN | ▲ | | | | ▼ RP | | | | | | ▼ | | ▲ n-3; PUFA
Lindsay, 2022;^21^ AHEI-2010 | ▲ | | ▲ LN | ▲ | ▼ | LN | ▲ | | | | ▼ RP | | | | | | ▼ | | ▲ n-3; PUFA | ▼ TFA | | ◄
Rifas-Shiman, 2009;^29^ Alternate HEI-P | ▲ | | | ▲ | | | | | | ▲ W:R | W:R | W:R | | | | | | | ▲ PUFA: SFA | ▼ TFA | PUFA:SFA | | | | ▲
Sauder, 2016;^30^ HEI-2005 | ▲ | | ▲ | ▲ | Fr | | ▲ ▲ G | G | G | | ▲ M | M | | ▲ | | | ▼ AS | AS | ▲ | | ▼ | ▼ | ▼
Tryggvadottir, 2016;^32^ Icelandic HEI | ▲ | | | ▲ | | ▲ | ▲ | | | ▲ | | | | | | | ▼ | | ▲ | | | | | | ▲
Yee, 2020;^34^ HEI-2010 | ▲ | | ▲ PRO | ▲ | Fr | PRO | ▲ | | ▼ | PRO | PRO | PRO | PRO | ▲ | | | ▼ AS | AS | ▲ | | ▼ | ▼ | ▼
Fulay, 2018;^11^ DASH | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Fulay, 2018;^11^ DASH OMNI | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | ▲ MUFA +PUFA | | | | ▼
Li, 2021;^19^ DASH | ▲ | | ▲ LN | ▲ | Fr | LN | ▲ | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Ding, 2021;^6^ CDGCI-PW | ▲ | ▲ | ▲ | | | ▲ N | | ▲ | | ▲ S | ▲R | ▲ | | ▲ | | | | ▼ | | | | | ▲ | | | ▼
Hillesund, 2018;^15^ NFFD Diet | ▲ | | | ▲ | | | | | | | | | | | | | ▼ AS | AS | | | | | ▼ | | ▲ | ▼
Hrolfsdottir, 2019;^16^ Dietary risk score | | | | | | | ▲ | | | | ▼ P | | | ▲ | | | ▼ | ▼ | | | | | | | ▲ | ▼
Meinila, 2017;^24^ HFII | ▲ | | | ▲ | | | ▲ | | | ▲ F | | | | | | | ▼ | | ▲ ▲ | | | | | | | ▼
Ruiz-Gracia, 2016;^45^ Nutrition variables at risk | | | | | ▼ JSD | ▲ N | | | ▼ | | | | | | | | JSD | ▼
Wang, 2021;^33^ PDI | ▲ PL | | PL | PL | | PL | PL | | PL | ▼ AN | AN | AN | AN | AN | | | | PL | PL
Wang, 2021;^33^ hPDI | ▲ HPL | ▼ UPL | HPL | HPL | UPL | | HPL | | UPL | ▼ AN | AN | AN | AN | AN | | | UPL | UPL | HPL | | AN | | | HPL | | ▼
Wang, 2021;^33^ uPDI | ▼ HPL | ▲ UPL | HPL | HPL | UPL | | HPL | | UPL | ▼ AN | AN | AN | AN | AN | | | UPL | UPL | HPL | | AN | | | HPL | | ▼
Factor/Cluster
Angali, 2020;^1^ High fat-fast food | | | | | | | ▲ | ▲ | | | ▲ RP | | | | | ▲ | ▲
Angali, 2020;^1^ Vegetable-fruits and protein | ▲ | | | ▲ | | | | | | | ▲ RW | RW | | | ▲ | | | | ▲
de Seymour, 2022;^5^ Fish, poultry and vegetables-based | ▲ | | ▲ | ▲ | | ▲ N | | ▲ | | ▲ | ▲ R | ▲ | ▲ | ▲ | | | | | | | | | | | ▲
de Seymour, 2022;^5^ Pasta, sweetened beverages, oils and condiments-based | | | | | | | | ▲ | | | | | | | | | ▲ | | ▲ OC | | OC | | | | ▲
Du, 2017;^7^ Western | | | | | | | | | | | | ▲ | | ▲ | | | | | | | | | | | ▲
Du, 2017;^7^ Traditional | ▲ | ▲ | | | | | | | ▲ | | ▲ R
Du, 2017;^7^ Mixed | ▲ | | | | | | | | | | ▲ R
Du, 2017;^7^ Prudent | ▲ | | | | | | | | | ▲ F
Du, 2017;^7^ DP 1 | ▲ | | | | | | | | ▲ | | ▲ R
Du, 2017;^7^ DP 2 | ▲ | | | | | | | | ▲ | ▲ F
Du, 2017;^7^ DP 3 | | | | | | | | | | | | | | ▲ | | | | | | | | | | | ▲
Du, 2017;^7^ DP 4 | | ▲ | | | | | | | | | | ▲
Flynn, 2016;^10^ Fruit & Veg | ▲ | | ▲ | ▲ | | | | | | | | | | ▲ Y
Flynn, 2016;^10^ African/Caribbean | | ▲ | | ▲ | | | | ▲ | | ▲ F | ▲ RW | RW
Flynn, 2016;^10^ Processed | ▲ | ▲ | | | | | | | | | ▲ P | | | | | | ▲ | ▲ | | | | | | | ▲
Flynn, 2016;^10^ Snacks | | | | | | | | | | | | | | ▲ CH | | | | ▲
Hajianfar, 2018;^12^ Healthy | ▲ | | | ▲ | | ▲ N | | | | ▲ F | ▲ R | ▲ | ▲ | | ▲ | | | | ▲ | | | | | | ▲
Hajianfar, 2018;^12^ Western | | ▲ | ▲ | ▲ | ▲ | ▲ N | ▲ | | | ▲ F | ▲ P | | ▲ | | | ▲ | ▲ ▲ AS | ▲ AS | | | ▲ | | | ▲ C | ▲
Hajianfar, 2018;^12^ Traditional | ▲ | | | | | | | | ▲ | | | | | | | | ▲ AS | AS | ▲ | | | | ▲ | ▲ T | ▲
He, 2015;^13^ Vegetable | ▲ | | ▲ | ▲ | | ▲ N | | | | | | | | | | | | | ▲
He, 2015;^13^ Protein-rich | ▲ | | | | | | | | ▲ | ▲ F | ▲ RP | ▲ | ▲ | | | | | | | | | | | | ▲
He, 2015;^13^ Prudent | ▼ | | | ▲ | | ▲ N | | | | ▲ F | ▼P | | ▲ | ▲ | | | ▼ | | | | | | | | ▲
He, 2015;^13^ Sweets and seafood | ▼ | | | | | | | | ▼ | ▲ F | | | | | | | ▲ | ▲
Hehua, 2021;^14^ Healthy | ▲ | ▲ | ▲ | ▲ | | ▲ N | ▲ | | | ▲ F | | | ▲ | ▲ | | | ▲ | ▲
Hehua, 2021;^14^ Sweet foods | ▲ FVJ | | | | FVJ
Hehua, 2021;^14^ Animal foods | | | | | | | | | | | ▲ RP | | ▲
Hehua, 2021;^14^ Traditional | ▲ | | | | | | | | | | | | | | | | | | | | | | | | ▲ ▲
Hu, 2019;^17^ Traditional-TFD | ▲ | ▲ | | ▲ | | ▲ N | | ▲ | | | ▲R | | ▲
Hu, 2019;^17^ Sweet foods-TFD | | | | ▲ | | | | | | ▲ S | ▲R | | | | | | ▲ | ▲
Hu, 2019;^17^ Fried food-beans-TFD | | | ▲ | | | | | | | | ▼R | | | ▲ | | | | | | | | | | | ▲
Hu, 2019;^17^ Whole grainseafood-TFD | ▲ | | | | | ▲ N | ▲ | ▼ | | ▲ S | | | ▼ | ▼
Hu, 2019;^17^ Fish-seafood-FFQ | ▲ | | | | | | | | | ▲ | ▲R
Hu, 2019;^17^ Protein-sweets-FFQ | | | ▲ | | | ▲ N | | | | | | | ▲ | ▲ ▲ | | | | ▲
Hu, 2019;^17^ Traditional-FFQ | ▲ | | | ▲ | | ▲ N | | ▲
Mak, 2018;^22^ Plant-based | ▲ | ▲ | ▲ | ▲ | | | | | | | | ▼
Mak, 2018;^22^ Meat-based | ▲ | | | | | | | | | ▲ S | | ▲ RP
Mak, 2018;^22^ High protein-low starch | | | | | | | | ▼ | | ▲ F | | ▲ | ▲ | ▲
Miele, 2021;^25^ Obesogenic | | | | | | | | | ▲ | | | | | | | | | ▲ | ▲ Fats | Fats | Fats | | | | ▲ UP
Miele, 2021;^25^ Intermediate | | | | | | | | | ▼ | | | | | | | | | ▼ | ▼ Fats | Fats | Fats | | | | | ▼ UP
Miele, 2021;^25^ Vegetarian | ▲ | | | ▲ | | | | | | | | | | ▲
Miele, 2021;^25^ Protein | | | ▲ | | | | | | | | ▲ | | ▲ | | | | | | | | | | | | | ▼
Miele, 2021;^25^ Traditional | | | ▲ | | | | | | | | ▲ M | M | ▲ | | | | | | | | | | | | ▲
Pajunen, 2021;^26^ Healthier | ▲ | | | ▲ | | | ▲ | ▲ | | ▲ | | ▲ | ▲ | ▲ CH | | | | | ▲ | | | | | ▲
Pajunen, 2021;^26^ Unhealthier | | | | ▲ | | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | | | | ▲ | | | | | | | ▲
Paknahad, 2019;^27^ High Carbohydrate-Lower Fat | ▲ | ▲ ▲ FF | ▲ | ▲ | | | | ▲ | | | | | ▲ | | ▲ | | | | | | | | | | ▲
Paknahad, 2019;^27^ High Carbohydrate-Higher Fat | ▲ | | ▲ | | | | | | | ▲ F | | | | ▲ Y | | ▲ | | | | | ▲ | | | | ▲
Paknahad, 2019;^27^ High fiber | ▲ | | | ▲
Radesky, 2008;^28^ Prudent | ▲ | | ▲ | ▲ | | | ▲ | | | ▲ F | | ▲ | ▲ | | | | | | ▲ SD | | SD
Radesky, 2008;^28^ Western | | ▲ FF | | | | | | | ▲ | | ▲ P | | | | | ▲ | ▲ | ▲ | | | ▲
Tryggvadottir, 2016;^32^ Prudent | ▲ | ▼ FF | | ▲ | | ▲ | | ▲ | | ▲ S | | | ▲ | | | | ▼ | | ▲ | | | | | ▲
Yong, 2020;^35^ DP 1 | ▲ | | ▲ | ▲ | | ▲ | | | | | | | ▲ | ▲
Yong, 2020;^35^ DP 3 | | | | | | | | ▲ | | ▲ | ▲ RW | RW | | | | | | ▲ | ▲ OF | OF | OF | | | | ▲
Yong, 2020;^35^ DP 4 | ▲ | | ▲ | ▲ | | ▲
Yong, 2020;^35^ DP 6 | | | | | | | | ▲ | | ▲ | ▲P RW | RW | ▲ | ▲ | | | | ▲ | | | | | | | ▲
Zhou, 2018;^36^ Beansvegetables | ▲ | | ▲ | ▲
Zhou, 2018;^36^ Nuts-whole grains | | | | | | ▲ N | ▲ | | | | | | | ▲
Zhou, 2018;^36^ Organ-poultryseafood | | | | | | | | | | ▲ S | ▲R | ▲
Zhou, 2018;^36^ Fish-meat-eggs | | | | | | | | | | ▲ F | ▲R | | ▲
Zhou, 2018;^36^ Rice-wheat-fruits | | | | ▲ | | | ▲