# Appendix 5 Excluded articles

The existing systematic review^*^ for this question included 11 articles. However, after applying the inclusion and exclusion criteria established for the update to that review, only 5 remained eligible for inclusion. The following articles were excluded from the existing systematic review due to updated eligibility criteria:

1. Clapp JF, 3rd. Effect of dietary carbohydrate on the glucose and insulin response to mixed caloric intake and exercise in both nonpregnant and pregnant women. Diabetes Care 1998;21 Suppl 2:B107-12. (Excluded for Outcome)
2. Schoenaker DA, Soedamah-Muthu SS, Callaway LK, Mishra GD. Pre-pregnancy dietary patterns and risk of gestational diabetes mellitus: results from an Australian population-based prospective cohort study. Diabetologia 2015;58(12):2726-35. (Excluded for Life Stage)
3. Schoenaker DA, Soedamah-Muthu SS, Mishra GD. Quantifying the mediating effect of body mass index on the relation between a Mediterranean diet and development of maternal pregnancy complications: the Australian Longitudinal Study on Women’s Health. Am J Clin Nutr 2016;104(3):638-45. (Excluded for Life Stage)
4. Tobias DK, Zhang C, Chavarro J, Bowers K, Rich-Edwards J, Rosner B, Mozaffarian D, Hu FB. Pre-pregnancy adherence to dietary patterns and lower risk of gestational diabetes mellitus. Am J Clin Nutr 2012;96(2):289-95. (Excluded for Life Stage)
5. Zhang C, Schulze MB, Solomon CG, Hu FB. A prospective study of dietary patterns, meat intake and the risk of gestational diabetes mellitus. Diabetologia 2006;49(11):2604-13. (Excluded for Life Stage)
6. Zhang C, Tobias DK, Chavarro JE, Bao W, Wang D, Ley SH, Hu FB. Adherence to healthy lifestyle and risk of gestational diabetes mellitus: prospective cohort study. BMJ 2014;349:g5450. (Excluded for Life Stage)

* Raghavan R, Dreibelbis C, Kingshipp BJ, . Dietary Patterns before and during Pregnancy and Risk of Gestational Diabetes Mellitus: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0102

The following tables list the articles excluded after full-text screening for the updated systematic review literature search (Appendix 4) Articles excluded from Search A are in Table A 2 and articles excluded from Search B are in Table A 3. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 12 Search A articles excluded after full text screening

| Citation | Rationale
1 | Alamolhoda, SH, Simbar, M, Mirmiran, P, Mirabi, P. The effectiveness of low trans-fatty acids dietary pattern in pregnancy and the risk of gestational diabetes mellitus. Caspian J Intern Med. 2019. 10:197-204. doi:10.22088/cjim.10.2.197 | Intervention/Exposure
2 | Allman, BR, Diaz Fuentes, E., Williams, KD, Turner, DE, Andres, A, Børsheim, E. Obesity Status Affects the Relationship Between Protein Intake and Insulin Sensitivity in Late Pregnancy. Nutrients. 2019. 11:2190. doi:10.3390/nu11092190 | Intervention/Exposure
3 | Anand, SS, Gupta, M, Teo, KK, Schulze, KM, Desai, D, Abdalla, N, Zulyniak, M, de Souza, R, Wahi, G, Shaikh, M, Beyene, J, de Villa, E, Morrison, K, McDonald, SD, Gerstein, H. Causes and consequences of gestational diabetes in South Asians living in Canada: results from a prospective cohort study. CMAJ Open. 2017. 5:E604-e611. doi:10.9778/cmajo.20170027 | Study Design
4 | Arredondo, A, Torres, C, Orozco, E, Pacheco, S, Huang, F, Zambrano, E, Bolaños-Jiménez, F. Socio-economic indicators, dietary patterns, and physical activity as determinants of maternal obesity in middle-income countries: Evidences from a cohort study in Mexico. International Journal of Health Planning & Management. 2019. 34:e713-e725. doi:10.1002/hpm.2684 | Outcome; Comparator
5 | Arvizu, M, Afeiche, MC, Hansen, S, Halldorsson, TF, Olsen, SF, Chavarro, JE. Fat intake during pregnancy and risk of preeclampsia: a prospective cohort study in Denmark. Eur J Clin Nutr. 2019. 73:1040-1048. doi:10.1038/s41430-018-0290-z | Intervention/Exposure
6 | Assaf-Balut, C, Garcia de la Torre, N, Durán, A, Bordiu, E, Del Valle, L, Familiar, C, Valerio, J, Jimenez, I, Herraiz, MA, Izquierdo, N, Runkle, I, de Miguel, MP, Montañez, C, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. An Early, Universal Mediterranean Diet-Based Intervention in Pregnancy Reduces Cardiovascular Risk Factors in the “Fourth Trimester”. J Clin Med. 2019. 8. doi:10.3390/jcm8091499 | Study Design
7 | Barabash, A, Valerio Deogracia, J, Assaf-Balut, C, Del Valle, L, De La Torre, NG, Bordiu, E, Duran, A, Fuentes, M, Ines Sr, J, Cuesta, M, Rubio, MA, Calle, AL. 193-LB: Levels of Adherence to a Mediterranean Diet and Risk of Gestational Diabetes Mellitus: Modulation Effects of MTNRB1_rs10830963, TCFTL2_rs7903146, and MC4R_rs17782313 Gene Polymorphisms. Diabetes. 2019. 68. doi:10.2337/db19-193-LB | Publication Status
8 | Bartáková, V, Kuricová, K, Zlámal, F, Bělobrádková, J, Kaňková, K. Differences in food intake and genetic variability in taste receptors between Czech pregnant women with and without gestational diabetes mellitus. Eur J Nutr. 2018. 57:513-521. doi:10.1007/s00394-016-1334-6 | Study Design
9 | Broekhuizen, K, Simmons, D, Devlieger, R, van Assche, A, Jans, G, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Desoye, G, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LL, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Snoek, FJ, Jelsma, JGM, Bosmans, JE, van Poppel, MNM, van Dongen, JM. Cost-effectiveness of healthy eating and/or physical activity promotion in pregnant women at increased risk of gestational diabetes mellitus: economic evaluation alongside the DALI study, a European multicenter randomized controlled trial. Int J Behav Nutr Phys Act. 2018. 15:23. doi:10.1186/s12966-018-0643-y | Intervention/Exposure
10 | Bruno, R, Petrella, E, Bertarini, V, Pedrielli, G, Neri, I, Facchinetti, F. Adherence to a lifestyle programme in overweight/obese pregnant women and effect on gestational diabetes mellitus: a randomized controlled trial. Matern Child Nutr. 2017. 13. doi:10.1111/mcn.12333 | Intervention/Exposure
11 | Carlos, S, De La Fuente-Arrillaga, C, Bes-Rastrollo, M, Razquin, C, Rico-Campà, A, Martínez-González, MA, Ruiz-Canela, M. Mediterranean diet and health outcomes in the SUN cohort. Nutrients. 2018. 10. doi:10.3390/nu10040439 | Study Design; Data Overlap
12 | Carolan-Olah, M, Sayakhot, P. A randomized controlled trial of a web-based education intervention for women with gestational diabetes mellitus. Midwifery. 2019. 68:39-47. doi:10.1016/j.midw.2018.08.019 | Health Status; Life Stage
13 | Chen, Q, Feng, Y, Yang, H, Wu, W, Zhang, P, Wang, K, Wang, Y, Ko, J, Shen, J, Guo, L, Zhao, F, Du, W, Ru, S, Wang, S, Zhang, Y. A Vitamin Pattern Diet Is Associated with Decreased Risk of Gestational Diabetes Mellitus in Chinese Women: Results from a Case Control Study in Taiyuan, China. J Diabetes Res. 2019. 2019:5232308. doi:10.1155/2019/5232308 | Study Design
14 | Chen, X, de Seymour, JV, Han, TL, Xia, Y, Chen, C, Zhang, T, Zhang, H, Baker, PN. Metabolomic biomarkers and novel dietary factors associated with gestational diabetes in China. Metabolomics. 2018. 14:149. doi:10.1007/s11306-018-1445-6 | Study Design
15 | Compher, C, Elovitz, MA, Parry, S, Chittams, J, Griffith, CJ. 330: Diet pattern is associated with an increased risk of hypertensive disorders of pregnancy. American Journal of Obstetrics & Gynecology. 2018. 218:S206-S206. doi:10.1016/j.ajog.2017.10.266 | Publication Status
16 | de la Torre, NG, Assaf-Balut, C, Jiménez Varas, I, Del Valle, L, Durán, A, Fuentes, M, Del Prado, N, Bordiú, E, Valerio, JJ, Herraiz, MA, Izquierdo, N, Torrejón, MJ, Cuadrado, MA, de Miguel, P, Familiar, C, Runkle, I, Barabash, A, Rubio, MA, Calle-Pascual, AL. Effectiveness of Following Mediterranean Diet Recommendations in the Real World in the Incidence of Gestational Diabetes Mellitus (GDM) and Adverse Maternal-Foetal Outcomes: A Prospective, Universal, Interventional Study with a Single Group. The St Carlos Study. Nutrients. 2019. 11. doi:10.3390/nu11061210 | Comparator
17 | Deniz, ÇD, Özler, S, Sayın, FK, Eryılmaz, MA. Associations between night eating syndrome and metabolic parameters in pregnant women. Turkish Journal of Obstetrics and Gynecology. 2019. 16:107-111. doi:10.4274/tjod.galenos.2019.77864 | Intervention/Exposure
18 | Donazar-Ezcurra, M, Lopez-Del Burgo, C, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, de Irala, J, Bes-Rastrollo, M. Pre-pregnancy adherences to empirically derived dietary patterns and gestational diabetes risk in a Mediterranean cohort: the Seguimiento Universidad de Navarra (SUN) project. Br J Nutr. 2017. 118:715-721. doi:10.1017/s0007114517002537 | Life Stage
19 | Donazar-Ezcurra, M, Lopez-Del Burgo, C, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, de Irala, J, Bes-Rastrollo, M. Soft drink consumption and gestational diabetes risk in the SUN project. Clin Nutr. 2018. 37:638-645. doi:10.1016/j.clnu.2017.02.005 | Intervention/Exposure
20 | Dong, JY, Kimura, T, Ikehara, S, Cui, M, Kawanishi, Y, Yamagishi, K, Ueda, K, Iso, H. Chocolate consumption and risk of gestational diabetes mellitus: The Japan Environment and Children’s Study. British Journal of Nutrition. 2019. 122:936-941. doi:10.1017/S0007114519001806 | Intervention/Exposure
21 | Duran, A, De La Torre, NG, Assaf-Balut, C, Del Valle, L, Ines, J, Valerio Deogracia, J, Bordiu, E, Fuentes, M, Barabash, A, Cuesta, M, Rubio, MA, Calle, AL. 194-LB: Effectiveness of Following Mediterranean Diet (MedDiet) Recommendations in the Real World in the Incidence of Gestational Diabetes Mellitus (GDM) and Adverse Maternal-Fetal Outcomes: A Prospective, Universal Interventional Study. Diabetes. 2019. 68. doi:10.2337/db19-194-LB | Publication Status
22 | Elvebakk, T, Mostad, IL, Mørkved, S, Salvesen, K. Dietary Intakes and Dietary Quality during Pregnancy in Women with and without Gestational Diabetes Mellitus-A Norwegian Longitudinal Study. Nutrients. 2018. 10. doi:10.3390/nu10111811 | Intervention/Exposure
23 | Emond, JA, Karagas, MR, Baker, ER, Gilbert-Diamond, D. Better Diet Quality during Pregnancy Is Associated with a Reduced Likelihood of an Infant Born Small for Gestational Age: An Analysis of the Prospective New Hampshire Birth Cohort Study. J Nutr. 2018. 148:22-30. doi:10.1093/jn/nxx005 | Confounders
24 | Englund-Ögge, L, Brantsæter, AL, Juodakis, J, Haugen, M, Meltzer, HM, Jacobsson, B, Sengpiel, V. Associations between maternal dietary patterns and infant birth weight, small and large for gestational age in the Norwegian Mother and Child Cohort Study. Eur J Clin Nutr. 2019. 73:1270-1282. doi:10.1038/s41430-018-0356-y | Outcome
25 | Epel, E, Laraia, B, Coleman-Phox, K, Leung, C, Vieten, C, Mellin, L, Kristeller, JL, Thomas, M, Stotland, N, Bush, N, Lustig, RH, Dallman, M, Hecht, FM, Adler, N. Effects of a Mindfulness-Based Intervention on Distress, Weight Gain, and Glucose Control for Pregnant Low-Income Women: A Quasi-Experimental Trial Using the ORBIT Model. Int J Behav Med. 2019. 26:461-473. doi:10.1007/s12529-019-09779-2 | Intervention/Exposure
26 | Fernández-Barrés, S, Vrijheid, M, Manzano-Salgado, CB, Valvi, D, Martínez, D, Iñiguez, C, Jimenez-Zabala, A, Riaño-Galán, I, Navarrete-Muñoz, EM, Santa-Marina, L, Tardón, A, Vioque, J, Arija, V, Sunyer, J, Romaguera, D. The Association of Mediterranean Diet during Pregnancy with Longitudinal Body Mass Index Trajectories and Cardiometabolic Risk in Early Childhood. J Pediatr. 2019. 206:119-127.e6. doi:10.1016/j.jpeds.2018.10.005 | Study Design
27 | Gadgil, MD, Ehrlich, SF, Zhu, Y, Brown, SD, Hedderson, MM, Crites, Y, Ferrara, A. Dietary Quality and Glycemic Control Among Women with Gestational Diabetes Mellitus. J Womens Health (Larchmt). 2019. 28:178-184. doi:10.1089/jwh.2017.6788 | Health Status
28 | Gicevic, S, Gaskins, AJ, Fung, TT, Rosner, B, Tobias, DK, Isanaka, S, Willett, WC. Evaluating pre-pregnancy dietary diversity vs. dietary quality scores as predictors of gestational diabetes and hypertensive disorders of pregnancy. PLoS One. 2018. 13:e0195103. doi:10.1371/journal.pone.0195103 | Life Stage
29 | Gnanendran, S, Porrett, J, Woods, C, Buttrose, M, Jukka, C, Hollins, J, Robson, S, de Costa, C. A randomised controlled trial of consumption of dark chocolate in pregnancy to reduce pre-eclampsia: Difficulties in recruitment, allocation and adherence. Australian & New Zealand Journal of Obstetrics & Gynaecology. 2018. 58:358-361. doi:10.1111/ajo.12694 | Intervention/Exposure; Publication Status
30 | Gonzalez-Nahm, S, Hoyo, C, Østbye, T, Neelon, B, Allen, C, Benjamin-Neelon, SE. Associations of maternal diet with infant adiposity at birth, 6 months and 12 months. BMJ Open. 2019. 9:e030186. doi:10.1136/bmjopen-2019-030186 | Outcome
31 | Goodarzi-Khoigani, M, Mazloomy Mahmoodabad, SS, Baghiani Moghadam, MH, Nadjarzadeh, A, Mardanian, F, Fallahzadeh, H, Dadkhah-Tirani, A. Prevention of Insulin Resistance by Dietary Intervention among Pregnant Mothers: A Randomized Controlled Trial. Int J Prev Med. 2017. 8:85. doi:10.4103/ijpvm.IJPVM_405_16 | Intervention/Exposure
32 | Goshtasebi, A, Hosseinpour-Niazi, S, Mirmiran, P, Lamyian, M, Moghaddam Banaem, L, Azizi, F. Pre-pregnancy consumption of starchy vegetables and legumes and risk of gestational diabetes mellitus among Tehranian women. Diabetes Res Clin Pract. 2018. 139:131-138. doi:10.1016/j.diabres.2018.02.033 | Intervention/Exposure
33 | Hamad, R, Collin, DF, Baer, RJ, Jelliffe-Pawlowski, LL. Association of Revised WIC Food Package With Perinatal and Birth Outcomes: A Quasi-Experimental Study. JAMA Pediatrics. 2019. 173:845-852. doi:10.1001/jamapediatrics.2019.1706 | Intervention/Exposure
34 | Harreiter, J, Simmons, D, Desoye, G, Corcoy, R, Adelantado, JM, Devlieger, R, Galjaard, S, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LLT, Dunne, F, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Mantaj, U, Hill, D, Jelsma, JGM, Snoek, FJ, Leutner, M, Lackinger, C, Worda, C, Bancher-Todesca, D, Scharnagl, H, van Poppel, MNM, Kautzky-Willer, A. Nutritional Lifestyle Intervention in Obese Pregnant Women, Including Lower Carbohydrate Intake, Is Associated With Increased Maternal Free Fatty Acids, 3-β-Hydroxybutyrate, and Fasting Glucose Concentrations: A Secondary Factorial Analysis of the European Multicenter, Randomized Controlled DALI Lifestyle Intervention Trial. Diabetes Care. 2019. 42:1380-1389. doi:10.2337/dc19-0418 | Intervention/Exposure
35 | Hellmuth, C, Lindsay, KL, Uhl, O, Buss, C, Wadhwa, PD, Koletzko, B, Entringer, S. Association of maternal prepregnancy BMI with metabolomic profile across gestation. Int J Obes (Lond). 2017. 41:159-169. doi:10.1038/ijo.2016.153 | Outcome
36 | Hezaveh, ZS, Feizy, Z, Dehghani, F, Sarbakhsh, P, Moini, A, Vafa, M. The Association between Maternal Dietary Protein Intake and Risk of Gestational Diabetes Mellitus. Int J Prev Med. 2019. 10:197. doi:10.4103/ijpvm.IJPVM_86_19 | Study Design
37 | Huang, L, Shang, L, Yang, W, Li, D, Qi, C, Xin, J, Wang, S, Yang, L, Zeng, L, Chung, MC. High starchy food intake may increase the risk of adverse pregnancy outcomes: a nested case-control study in the Shaanxi province of Northwestern China. BMC Pregnancy Childbirth. 2019. 19:362. doi:10.1186/s12884-019-2524-z | Outcome
38 | Huang, WQ, Lu, Y, Xu, M, Huang, J, Su, YX, Zhang, CX. Excessive fruit consumption during the second trimester is associated with increased likelihood of gestational diabetes mellitus: a prospective study. Sci Rep. 2017. 7:43620. doi:10.1038/srep43620 | Intervention/Exposure
39 | Jiang, F, Li, Y, Xu, P, Li, J, Chen, X, Yu, H, Gao, B, Xu, B, Li, X, Chen, W. The efficacy of the Dietary Approaches to Stop Hypertension diet with respect to improving pregnancy outcomes in women with hypertensive disorders. J Hum Nutr Diet. 2019. 32:713-718. doi:10.1111/jhn.12654 | Intervention/Exposure; Health Status; Outcome; Comparator
40 | Kozlowska, A, Jagielska, AM, Okreglicka, KM, Dabrowski, F, Kanecki, K, Nitsch-Osuch, A, Wielgos, M, Bomba-Opon, D. Dietary macronutrients and fluid intakes in a sample of pregnant women with either gestational diabetes or type 1 diabetes mellitus, assessed in comparison with Polish nutritional guidelines. Ginekol Pol. 2018. 89:659-666. doi:10.5603/GP.a2018.0111 | Study Design; Health Status
41 | Kunath, J, Günther, J, Rauh, K, Hoffmann, J, Stecher, L, Rosenfeld, E, Kick, L, Ulm, K, Hauner, H. Effects of a lifestyle intervention during pregnancy to prevent excessive gestational weight gain in routine care - the cluster-randomised GeliS trial. BMC Med. 2019. 17:5. doi:10.1186/s12916-018-1235-z | Intervention/Exposure
42 | Lamyian, M, Hosseinpour-Niazi, S, Mirmiran, P, Moghaddam Banaem, L, Goshtasebi, A, Azizi, F. Pre-Pregnancy Fast Food Consumption Is Associated with Gestational Diabetes Mellitus among Tehranian Women. Nutrients. 2017. 9. doi:10.3390/nu9030216 | Intervention/Exposure
43 | Lavie, M, Lavie, I, Maslovitz, S. Paleolithic diet during pregnancy-A potential beneficial effect on metabolic indices and birth weight. Eur J Obstet Gynecol Reprod Biol. 2019. 242:7-11. doi:10.1016/j.ejogrb.2019.08.013 | Comparator; Data Overlap
44 | Liang, Y, Gong, Y, Zhang, X, Yang, D, Zhao, D, Quan, L, Zhou, R, Bao, W, Cheng, G. Dietary Protein Intake, Meat Consumption, and Dairy Consumption in the Year Preceding Pregnancy and During Pregnancy and Their Associations With the Risk of Gestational Diabetes Mellitus: A Prospective Cohort Study in Southwest China. Front Endocrinol (Lausanne). 2018. 9:596. doi:10.3389/fendo.2018.00596 | Intervention/Exposure
45 | Liang, Z, Wang, L, Liu, H, Chen, Y, Zhou, T, Heianza, Y, Leng, J, Li, W, Yang, X, Shen, Y, Gao, R, Hu, G, Qi, L. Genetic susceptibility, lifestyle intervention and glycemic changes among women with prior gestational diabetes. Clin Nutr. 2020. 39:2144-2150. doi:10.1016/j.clnu.2019.08.032 | Intervention/Exposure; Country; Life Stage
46 | Looman, M, Geelen, A, Samlal, RAK, Heijligenberg, R, Klein Gunnewiek, JMT, Balvers, MGJ, Wijnberger, LDE, Brouwer-Brolsma, EM, Feskens, EJM. Changes in Micronutrient Intake and Status, Diet Quality and Glucose Tolerance from Preconception to the Second Trimester of Pregnancy. Nutrients. 2019. 11. doi:10.3390/nu11020460 | Study Design; Life Stage
47 | Marí-Sanchis, A, Díaz-Jurado, G, Basterra-Gortari, JF, de la Fuente-Arrillaga, C, Martínez-González, MA, Bes-Rastrollo, M. Association between pre-pregnancy consumption of meat, iron intake, and the risk of gestational diabetes: the SUN project. European Journal of Nutrition. 2018. 57:939-949. doi:10.1007/s00394-017-1377-3 | Intervention/Exposure
48 | Maslova, E, Hansen, S, Strøm, M, Halldorsson, T, Grunnet, LG, Vaag, AA, Olsen, SF. Fish Intake in Pregnancy and Offspring Metabolic Parameters at Age 9–16—Does Gestational Diabetes Modify the Risk?. Nutrients. 2018. 10:1534. doi:10.3390/nu10101534 | Intervention/Exposure
49 | Meinilä, J, Valkama, A, Koivusalo, SB, Rönö, K, Kautiainen, H, Lindström, J, Stach-Lempinen, B, Eriksson, JG, Erkkola, M. Association between diet quality measured by the Healthy Food Intake Index and later risk of gestational diabetes-a secondary analysis of the RADIEL trial. Eur J Clin Nutr. 2017. 71:913. doi:10.1038/ejcn.2017.66 | Publication Status
50 | Mendoza, LC, Harreiter, J, Simmons, D, Desoye, G, Adelantado, JM, Juarez, F, Chico, A, Devlieger, R, van Assche, A, Galjaard, S, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LLT, Tanvig, M, Lapolla, A, Dalfra, MG, Bertolotto, A, Mantaj, U, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Jelsma, JG, Snoek, FJ, van Poppel, MNM, Worda, C, Bancher-Todesca, D, Kautzky-Willer, A, Dunne, FP, Corcoy, R. Risk factors for hyperglycemia in pregnancy in the DALI study differ by period of pregnancy and OGTT time point. Eur J Endocrinol. 2018. 179:39-49. doi:10.1530/eje-18-0003 | Intervention/Exposure
51 | Mi, B, Wen, X, Li, S, Liu, D, Lei, F, Liu, R, Shen, Y, Chen, Y, Zeng, L, Liu, X, Dang, S, Yan, H. Vegetable dietary pattern associated with low risk of preeclampsia possibly through reducing proteinuria. Pregnancy Hypertens. 2019. 16:131-138. doi:10.1016/j.preghy.2019.04.001 | Study Design
52 | Mirmiran, P, Hosseinpour-Niazi, S, Moghaddam-Banaem, L, Lamyian, M, Goshtasebi, A, Azizi, F. Inverse relation between fruit and vegetable intake and the risk of gestational diabetes mellitus. Int J Vitam Nutr Res. 2019. 89:37-44. doi:10.1024/0300-9831/a000475 | Intervention/Exposure
53 | Mizgier, M, Jarzabek-Bielecka, G, Mruczyk, K. Maternal diet and gestational diabetes mellitus development. J Matern Fetal Neonatal Med. 2021. 34:77-86. doi:10.1080/14767058.2019.1598364 | Intervention/Exposure
54 | Nykjaer, C, Higgs, C, Greenwood, DC, Simpson, NAB, Cade, JE, Alwan, NA. Maternal fatty fish intake prior to and during pregnancy and risks of adverse birth outcomes: Findings from a british cohort. Nutrients. 2019. 11. doi:10.3390/nu11030643 | Intervention/Exposure
55 | O’Brien, CM, Louise, J, Deussen, A, Dodd, JM. In Overweight or Obese Pregnant Women, Maternal Dietary Factors are not Associated with Fetal Growth and Adiposity. Nutrients. 2018. 10. doi:10.3390/nu10070870 | Outcome
56 | Osorio-Yáñez, C, Gelaye, B, Qiu, C, Bao, W, Cardenas, A, Enquobahrie, DA, Williams, MA. Maternal intake of fried foods and risk of gestational diabetes mellitus. Ann Epidemiol. 2017. 27:384-390.e1. doi:10.1016/j.annepidem.2017.05.006 | Intervention/Exposure
57 | Parlapani, E, Agakidis, C, Karagiozoglou-Lampoudi, T, Sarafidis, K, Agakidou, E, Athanasiadis, A, Diamanti, E. The Mediterranean diet adherence by pregnant women delivering prematurely: association with size at birth and complications of prematurity. J Matern Fetal Neonatal Med. 2019. 32:1084-1091. doi:10.1080/14767058.2017.1399120 | Study Design
58 | Rohatgi, KW, Tinius, RA, Cade, WT, Steele, EM, Cahill, AG, Parra, DC. Relationships between consumption of ultra-processed foods, gestational weight gain and neonatal outcomes in a sample of US pregnant women. PeerJ. 2017. 5:e4091. doi:10.7717/peerj.4091 | Outcome
59 | Schoenaker, Dajm, Dodd, JM, Dodd, JM. Does preconception body mass index modify the effect of maternal diet on hypertensive disorders of pregnancy? BJOG: An International Journal of Obstetrics & Gynaecology. 2019. 126:674-674. doi:10.1111/1471-0528.15596 | Publication Status
60 | Sen, S, Rifas-Shiman, SL, Shivappa, N, Wirth, MD, Hebert, JR, Gold, DR, Gillman, MW, Oken, E. Dietary Inflammatory Potential during Pregnancy Is Associated with Lower Fetal Growth and Breastfeeding Failure: Results from Project Viva. Journal of Clinical Chiropractic Pediatrics. 2017. 16:1381-1381. doi:10.3945/jn.115.225581 | Intervention/Exposure
61 | Simmons, D, Devlieger, R, van Assche, A, Jans, G, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Desoye, G, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, L, Lapolla, A, Dalfrà, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Snoek, FJ, Jelsma, JG, van Poppel, MN. Effect of Physical Activity and/or Healthy Eating on GDM Risk: The DALI Lifestyle Study. J Clin Endocrinol Metab. 2017. 102:903-913. doi:10.1210/jc.2016-3455 | Intervention/Exposure
62 | Simões-Wüst, AP, Moltó-Puigmartí, C, Jansen, EH, van Dongen, MC, Dagnelie, PC, Thijs, C. Organic food consumption during pregnancy and its association with health-related characteristics: the KOALA Birth Cohort Study. Public Health Nutr. 2017. 20:2145-2156. doi:10.1017/s1368980017001215 | Intervention/Exposure
63 | Starling, AP, Sauder, KA, Kaar, JL, Shapiro, AL, Siega-Riz, AM, Dabelea, D. Maternal Dietary Patterns during Pregnancy Are Associated with Newborn Body Composition. J Nutr. 2017. 147:1334-1339. doi:10.3945/jn.117.248948 | Confounders
64 | Stuart, JJ, Tanz, LJ, Missmer, SA, Rimm, EB, Spiegelman, D, James-Todd, TM, Rich-Edwards, JW. High Blood Pressure During Pregnancy and Development of Risk Factors for Cardiovascular Disease. Ann Intern Med. 2018. 169. doi:10.7326/p18-0008 | Study Design; Publication Status
65 | Tajima, R, Yachi, Y, Tanaka, Y, Kawasaki, YA, Nishibata, I, Hirose, AS, Horikawa, C, Kodama, S, Iida, K, Sone, H. Carbohydrate intake during early pregnancy is inversely associated with abnormal glucose challenge test results in Japanese pregnant women. Diabetes/Metabolism Research & Reviews. 2017. 33:n/a-N.PAG. doi:10.1002/dmrr.2898 | Intervention/Exposure
66 | Tajirika-Shirai, R, Takimoto, H, Yokoyama, T, Kaneko, H, Kubota, T, Miyasaka, N. Effect of individualised dietary education at medical check-ups on maternal and fetal outcomes in pregnant Japanese women. Asia Pac J Clin Nutr. 2018. 27:607-616. doi:10.6133/apjcn.082017.01 | Study Design;; Intervention/Exposure
67 | Tielemans, MJ, Erler, NS, Franco, OH, Jaddoe, VWV, Steegers, EAP, Kiefte-de Jong, JC. Dietary acid load and blood pressure development in pregnancy: The Generation R Study. Clin Nutr. 2018. 37:597-603. doi:10.1016/j.clnu.2017.01.013 | Intervention/Exposure
68 | Valkama, AJ, Meinilä, J, Koivusalo, S, Lindström, J, Rönö, K, Stach-Lempinen, B, Kautiainen, H, Eriksson, JG. The effect of pre-pregnancy lifestyle counselling on food intakes and association between food intakes and gestational diabetes in high-risk women: results from a randomised controlled trial. J Hum Nutr Diet. 2018. 31:301-305. doi:10.1111/jhn.12547 | Intervention/Exposure
69 | Valkama, AJ, Meinilä, JM, Koivusalo, SB, Lindström, J, Rönö, K, Stach-Lempinen, B, Eriksson, JG. Diet quality as assessed by the Healthy Food Intake Index and relationship with serum lipoprotein particles and serum fatty acids in pregnant women at increased risk for gestational diabetes. Br J Nutr. 2018. 120:914-924. doi:10.1017/s0007114518002404 | Confounders
70 | Van Der Hoeven, T, Browne, JL, Uiterwaal, CSPM, Van Der Ent, CK, Grobbee, DE, Dalmeijer, GW. Antenatal coffee and tea consumption and the effect on birth outcome and hypertensive pregnancy disorders. PLoS ONE. 2017. 12. doi:10.1371/journal.pone.0177619 | Intervention/Exposure
71 | Wu, Y, Sun, G, Zhou, X, Zhong, C, Chen, R, Xiong, T, Li, Q, Yi, N, Xiong, G, Hao, L, Yang, N, Yang, X. Pregnancy dietary cholesterol intake, major dietary cholesterol sources, and the risk of gestational diabetes mellitus: A prospective cohort study. Clin Nutr. 2020. 39:1525-1534. doi:10.1016/j.clnu.2019.06.016 | Intervention/Exposure
72 | Zareei, S, Homayounfar, R, Naghizadeh, MM, Ehrampoush, E, Rahimi, M. Dietary pattern in pregnancy and risk of gestational diabetes mellitus (GDM). Diabetes Metab Syndr. 2018. 12:399-404. doi:10.1016/j.dsx.2018.03.004 | Study Design
73 | Zhu, Y, Hedderson, MM, Sridhar, S, Xu, F, Feng, J, Ferrara, A. Poor diet quality in pregnancy is associated with increased risk of excess fetal growth: a prospective multi-racial/ethnic cohort study. Int J Epidemiol. 2019. 48:423-432. doi:10.1093/ije/dyy285 | Confounders
74 | Zulyniak, MA, de Souza, RJ, Shaikh, M, Desai, D, Lefebvre, DL, Gupta, M, Wilson, J, Wahi, G, Subbarao, P, Becker, AB, Mandhane, P, Turvey, SE, Beyene, J, Atkinson, S, Morrison, KM, McDonald, S, Teo, KK, Sears, MR, Anand, SS. Does the impact of a plant-based diet during pregnancy on birth weight differ by ethnicity? A dietary pattern analysis from a prospective Canadian birth cohort alliance. BMJ Open. 2017. 7:e017753. doi:10.1136/bmjopen-2017-017753 | Outcome

Table A 13 Search B articles excluded after full text screening

| Citation | Rationale
1 | Effects of Western style or Mediterranean diet on insulin resistance markers in female BRCA1/2 mutation carriers (LIBRE STUDY). Clinical nutrition (Edinburgh, Scotland). 2019. 38:S99-S100. doi:10.1016/S0261-5614(19)32743-8 | Publication Status
2 | Efficacy of different prediabetes program models in improving clinical outcomes in people with prediabetes. Proceedings of the Nutrition Society. 2020. 79. doi:10.1017/S0029665120004711 | Publication Status
3 | Identification of education models to improve health outcomes in Arab women with pre-diabetes. Nutrients. 2019. 11. doi:10.3390/nu11051113 | Intervention/Exposure
4 | MED Diet May Lower Diabetes Risk. Environmental Nutrition. 2021. 44:1-1. | Publication Status
5 | Abdrabalnabi, AA, Rajaram, S, Bitok, E, Oda, K, Beeson, WL, Kaur, A, Cofan, M, Serra-Mir, M, Roth, I, Ros, E, etal, . Effects of supplementing the usual diet with a daily dose of walnuts for two years on metabolic syndrome and its components in an elderly cohort. Nutrients. 2020. 12. doi:10.3390/nu12020451 | Intervention/Exposure
6 | Actrn,. An investigation into the effect of a 12-week RCT comparing a low carbohydrate, high fat diet vs mainstream nutrition guidelines on metabolic health outcomes in overweight New Zealand Defence Force personnel. http://www.who.int/trialsearch/Trial2.aspx?TrialID=ACTRN12616001579482. 2016. | Publication Status
7 | Actrn,. Intervention with diet rich in two types of dietary fibre on glycemia, adipokines and lipid status in obese pre-diabetic subjects. http://www.who.int/trialsearch/Trial2.aspx?TrialID=ACTRN12613001118796. 2013. | Publication Status
8 | Adam, TC, Drummen, M, Macdonald, I, Jalo, E, Siig-Vestentoft, P, Martinez, JA, Handjiev-Darlenska, T, Brand-Miller, J, Poppitt, S, Stratton, G, Fogelholm, M, Pietiläinen, KH, Taylor, M, Navas-Carretero, S, Winkens, B, Handjiev, S, Muirhead, R, Silvestre, M, Swindell, N, Huttunen-Lenz, M, Schlicht, W, Lam, T, Sundvall, J, Råman, L, Feskens, E, Larssen, TM, Tremblay, A, Raben, A, Westerterp-Plantenga, M. Association of Psychobehavioral Variables With HOMA-IR and BMI Differs for Men and Women With Prediabetes in the PREVIEW Lifestyle Intervention. Diabetes care. 2021. doi:10.2337/dc21-0059 | Intervention/Exposure
9 | Aghaei, N, Rouhani, MH, Tabatabaei, F, Larijani, B, Azadbakht, L. Effect of diverse low energy-dense versus healthy diet on metabolic outcomes in overweight/obese adolescents: A randomized controlled trial. Progress in Nutrition. 2019. 21:122-129. doi:10.23751/pn.v21i1-S.5721 | Study Duration
10 | Ahmad, S, Moorthy, MV, Demler, OV, Hu, FB, Ridker, PM, Chasman, DI, Mora, S. Assessment of Risk Factors and Biomarkers Associated With Risk of Cardiovascular Disease Among Women Consuming a Mediterranean Diet. JAMA Network Open. 2018. 1. | Outcome
11 | Ainscough, KM, O’Brien, EC, Lindsay, KL, Kennelly, MA, O’Sullivan, EJ, O’Brien, OA, McCarthy, M, De Vito, G, McAuliffe, FM. Nutrition, Behavior Change and Physical Activity Outcomes From the PEARS RCT-An mHealth-Supported, Lifestyle Intervention Among Pregnant Women With Overweight and Obesity. Front Endocrinol (Lausanne). 2019. 10:938. doi:10.3389/fendo.2019.00938 | Intervention/Exposure; Outcome
12 | Aittola, K, Karhunen, L, Männikkö, R, Järvelä-Reijonen, E, Mikkonen, S, Absetz, P, Kolehmainen, M, Schwab, U, Harjumaa, M, Lindström, J, Lakka, T, Tilles-Tirkkonen, T, Pihlajamäki, J. Enhanced eating competence is associated with improved diet quality and cardiometabolic profile in finnish adults with increased risk of type 2 diabetes. Nutrients. 2021. 13. | Intervention/Exposure
13 | Akpulat, S, Gülsoy Kirnap, N, Pfeiffer, A. The effects of low-carbohydrate diet and protein-rich mixed diet on insulin sensitivity, basal metabolic rate and metabolic parameters in obese patients. Turkish Journal of Endocrinology and Metabolism. 2020. 24:206-213. doi:10.25179/tjem.2019-72200 | Intervention/Exposure; Comparator
14 | Al Aamri, KS, Alrawahi, AH, Al Busaidi, N, Al Githi, MS, Al Jabri, K, Al Balushi, F, Ronquillo-Talara, R, Al Balushi, S, Waly, DM. The effect of low-carbohydrate ketogenic diet in the management of obesity compared with low caloric, low-fat diet. Clinical Nutrition ESPEN. 2022. | Intervention/Exposure
15 | Al Wattar H, B, Dodds, J, Placzek, A, Beresford, L, Spyreli, E, Moore, A, Gonzalez Carreras, FJ, Austin, F, Murugesu, N, Roseboom, TJ, Bes-Rastrollo, M, Hitman, GA, Hooper, R, Khan, KS, Thangaratinam, S. Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. PLoS Medicine. 2019. 16. doi:10.1371/journal.pmed.1002857 | Data Overlap
16 | Alamolhoda, SH, Simbar, M, Mirmiran, P, Mirabi, P. The effectiveness of low trans-fatty acids dietary pattern in pregnancy and the risk of gestational diabetes mellitus. Caspian Journal of Internal Medicine. 2019. 10:197-204. doi:10.22088/cjim.10.2.197 | Intervention/Exposure
17 | Albert SL, Massar RE, Correa L, Kwok L, Joshi S, Shah S, Boas R, Alcalá HE, McMacken M. Change in cardiometabolic risk factors in a pilot safety-net plant-based lifestyle medicine program. 10. | Intervention/Exposure
18 | Al-Daghri, NM, Amer, OE, Hameidi, A, Alfawaz, H, Alharbi, M, Khattak, MNK, Alnaami, AM, Aljohani, NJ, Alkhaldi, G, Wani, K, Sabico, S. Effects of a 12-Month Hybrid (In-Person + Virtual) Education Program in the Glycemic Status of Arab Youth. Nutrients. 2022. 14. | Intervention/Exposure
19 | Aldubayan, MA, Pigsborg, K, Gormsen, SMO, Serra, F, Palou, M, Galmés, S, Palou-March, A, Favari, C, Wetzels, M, Calleja, A, Rodríguez Gómez, MA, Castellnou, MG, Caimari, A, Galofré, M, Suñol, D, Escoté, X, Alcaide-Hidalgo, JM, M del Bas, J, Gutierrez, B, Krarup, T, Hjorth, MF, Magkos, F. A double-blinded, randomized, parallel intervention to evaluate biomarker-based nutrition plans for weight loss: The PREVENTOMICS study. Clinical Nutrition. 2022. 41:1834. | Intervention/Exposure; Study Duration
20 | Alfawaz, H, Naeef, AF, Wani, K, Khattak, MNK, Sabico, S, Alnaami, AM, Al-Daghri, NM. Improvements in Glycemic, Micronutrient, and Mineral Indices in Arab Adults with Pre-Diabetes Post-Lifestyle Modification Program. Nutrients. 2019. 11. doi:10.3390/nu11112775 | Intervention/Exposure
21 | Aljefree, NM, Almoraie, NM, Shatwan, IM. Association of two types of dietary pattern scores with cardiovascular disease risk factors and serum 25 hydroxy vitamin D levels in Saudi Arabia. Food Nutr Res. 2021. 65. doi:10.29219/fnr.v65.5481 | Study Design
22 | Al-Salmi, N, Cook, P, D’souza, MS. Diet Adherence among Adults with Type 2 Diabetes Mellitus: A Concept Analysis. Oman Medical Journal. 2022. 37. | Health Status
23 | Amer, OE, Sabico, S, Alfawaz, HA, Aljohani, N, Hussain, SD, Alnaami, AM, Wani, K, Al-Daghri, NM. Reversal of Prediabetes in Saudi Adults: results from an 18 Month Lifestyle Intervention. Nutrients. 2020. 12. doi:10.3390/nu12030804 | Intervention/Exposure
24 | Amerikanou C, Kleftaki SA, Valsamidou E, Tzavara C, Gioxari A, Kaliora AC. Dietary Patterns, Cardiometabolic and Lifestyle Variables in Greeks with Obesity and Metabolic Disorders. 14. | Study Design
25 | Aminianfar, A, Soltani, S, Hajianfar, H, Azadbakht, L, Shahshahan, Z, Esmaillzadeh, A. The association between dietary glycemic index and load and risk of gestational diabetes mellitus: A prospective study. Diabetes Res Clin Pract. 2020. 170:108469. doi:10.1016/j.diabres.2020.108469 | Intervention/Exposure
26 | Anand, C, Kranz, R-M, Husain, S, Koeder, C, Schoch, N, Alzughayyar, D-K, Gellner, R, Hengst, K, Englert, H. Bridging the gap between science and society: Long-term effects of the Healthy Lifestyle Community Programme (HLCP, cohort 1) on weight and the metabolic risk profile: A controlled study. BMJ Nutrition, Prevention and Health. 2022. | Intervention/Exposure; Study Duration; Comparator
27 | Anand, SS, Gupta, M, Teo, KK, Schulze, KM, Desai, D, Abdalla, N, Zulyniak, M, de Souza, R, Wahi, G, Shaikh, M, Beyene, J, de Villa, E, Morrison, K, McDonald, SD, Gerstein, H. Causes and consequences of gestational diabetes in South Asians living in Canada: results from a prospective cohort study. CMAJ open. 2017. 5:E604. | Study Design
28 | Andersen E, van der Ploeg HP, van Mechelen W, Gray CM, Mutrie N, van Nassau F, Jelsma JGM, Anderson AS, Silva MN, Pereira HV, McConnachie A, Sattar N, Sørensen M, Røynesdal ØB, Hunt K, Roberts GC, Wyke S, Gill JMR. Contributions of changes in physical activity, sedentary time, diet and body weight to changes in cardiometabolic risk. 18. | Intervention/Exposure; Outcome
29 | Antoni, R, Johnston, KL, Steele, C, Carter, D, Robertson, MD, Capehorn, MS. Efficacy of an intermittent energy restriction diet in a primary care setting. European Journal of Nutrition. 2020. 59:2805-2812. doi:10.1007/s00394-019-02098-y | Intervention/Exposure
30 | Aqeel, MM, Guo, J, Lin, L, Gelfand, SB, Delp, EJ, Bhadra, A, Richards, EA, Hennessy, E, Eicher-Miller, HA. Temporal Dietary Patterns Are Associated with Obesity in US Adults. J Nutr. 2020. 150:3259-3268. doi:10.1093/jn/nxaa287 | Study Design
31 | Aridi, YS, Walker, JL, Roura, E, Wright, ORL. Adherence to the Mediterranean Diet and Chronic Disease in Australia: National Nutrition and Physical Activity Survey Analysis. Nutrients. 2020. 12. doi:10.3390/nu12051251 | Study Design
32 | Aro, A, Kauppinen, A, Kivinen, N, Selander, T, Kinnunen, K, Tuomilehto, J, KeinÖnen-Kiukaanniemi, S, LindstrÖm, J, Uusitupa, M, Kaarniranta, K. Life style intervention improves retinopathy status—the finnish diabetes prevention study. Nutrients. 2019. 11. doi:10.3390/nu11071691 | Intervention/Exposure; Outcome
33 | Asemi, Z, Tabassi, Z, Samimi, M, Fahiminejad, T, Esmaillzadeh, A. Favourable effects of the Dietary Approaches to Stop Hypertension diet on glucose tolerance and lipid profiles in gestational diabetes: A randomised clinical trial. British Journal of Nutrition. 2013. 109:2024. | Health Status
34 | Asemi, Z, Tabassi, Z, Samimi, M, Fahiminejad, T, Esmaillzadeh, A. Favorable effects of the Dietary Approaches to Stop Hypertension diet on glucose tolerance and lipid profiles in gestational diabetes: a randomised clinical trial - Expression of concern. Br J Nutr. 2021. 1. doi:10.1017/S0007114521002002 | Study Design
35 | Asghari G, Mirmiran P, Rezaeemanesh A, Mahdavi M, Azizi F, Hadaegh F. Changes in ideal cardiovascular health among Iranian adolescents: 2007-2008 to 2015-2017. 22. | Study Design; Intervention/Exposure
36 | Assaf-Balut, C, de la Torre, NG, Durán, A, Bordiu, E, del Valle, L, Familiar, C, Valerio, J, Jimenez, I, Herraiz, MA, Izquierdo, N, Runkle, I, de Miguel, MP, Montañez, C, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. An early, universal mediterranean diet-based intervention in pregnancy reduces cardiovascular risk factors in the “fourth trimester”. Journal of Clinical Medicine. 2019. 8. doi:10.3390/jcm8091499 | Size of Study Groups; Data Overlap; Life Stage
37 | Assaf-Balut, C, de la Torre, NG, Fuentes, M, Durán, A, Bordiú, E, Del Valle, L, Valerio, J, Jiménez, I, Herraiz, MA, Izquierdo, N, Torrejón, MJ, de Miguel, MP, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. A high adherence to six food targets of the mediterranean diet in the late first trimester is associated with a reduction in the risk of materno-foetal outcomes: The st. carlos gestational diabetes mellitus prevention study. Nutrients. 2019. 11. doi:10.3390/nu11010066 | Intervention/Exposure; Data Overlap
38 | Assaf-Balut, C, García De La Torre, N, Duran, A, Fuentes, M, Bordiú, E, Del Valle, L, Familiar, C, Valerio, J, Jiménez, I, Herraiz, MA, Izquierdo, N, Torrejon, MJ, Cuadrado, Á M, Ortega, I, Illana, FJ, Runkle, I, De Miguel, P, Moraga, I, Montañez, C, Barabash, A, Cuesta, M, Rubio, MA, CallePascual, AL. A mediterranean diet with an enhanced consumption of extra virgin olive oil and pistachios improves pregnancy outcomes in women without gestational diabetes mellitus: A sub-analysis of the St. Carlos gestational diabetes mellitus prevention study. Annals of Nutrition and Metabolism. 2019. 74:69-79. doi:10.1159/000495793 | Data Overlap
39 | Azzini, E, Peluso, I, Intorre, F, Barnaba, L, Venneria, E, Foddai, MS, Ciarapica, D, Maiani, F, Raguzzini, A, Polito, A. Total and Plant Protein Consumption: The Role of Inflammation and Risk of Non-Communicable Disease. International Journal of Molecular Sciences. 2022. 23. | Study Design; Intervention/Exposure
40 | Badr HE, Saunders T, Carter A, Reyes Castillo L, Bayoumy O, Barrett M. Impact of Lifestyle Modification on Quality of Life in Patients with Metabolic Syndrome: Findings from the CHANGE Program Intervention Study in Prince Edward Island, Canada. 20. | Outcome; Comparator
41 | Baleato CL, Ferguson JJA, Oldmeadow C, Mishra GD, Garg ML. Plant-Based Dietary Patterns versus Meat Consumption and Prevalence of Impaired Glucose Intolerance and Diabetes Mellitus: A Cross-Sectional Study in Australian Women. 14. | Study Design
42 | Barabash, A, Valerio, JD, Garcia de la Torre, N, Jimenez, I, Del Valle, L, Melero, V, Assaf-Balut, C, Fuentes, M, Bordiu, E, Duran, A, Herraiz, MA, Izquierdo, N, Torrejon, MJ, de Miguel, P, Runkle, I, Rubio, MA, Calle-Pascual, AL. TCF7L2 rs7903146 polymorphism modulates the association between adherence to a Mediterranean diet and the risk of gestational diabetes mellitus. Metabol Open. 2020. 8:100069. doi:10.1016/j.metop.2020.100069 | Data Overlap
43 | Barker, Katelyn, Davy, Brenda. Is Consumption of Ultra-Processed Foods Associated with Cardiometabolic Risk?. Scan’s Pulse. 2021. 41:1-5. | Publication Status
44 | Barnard ND, Rembert E, Freeman A, Bradshaw M, Holubkov R, Kahleova H. Blood Type Is Not Associated with Changes in Cardiometabolic Outcomes in Response to a Plant-Based Dietary Intervention. 121. | Intervention/Exposure; Comparator
45 | Barnard, ND, Alwarith, J, Rembert, E, Brandon, L, Nguyen, M, Goergen, A, Horne, T, do Nascimento, GF, Lakkadi, K, Tura, A, Holubkov, R, Kahleova, H. A Mediterranean Diet and Low-Fat Vegan Diet to Improve Body Weight and Cardiometabolic Risk Factors: A Randomized, Cross-over Trial. J Am Coll Nutr. 2021. 1-13. doi:10.1080/07315724.2020.1869625 | Intervention/Exposure; Comparator
46 | Barrea, L, Muscogiuri, G, Pugliese, G, de Alteriis, G, Colao, A, Savastano, S. Metabolically healthy obesity (Mho) vs. metabolically unhealthy obesity (muo) phenotypes in pcos: Association with endocrine-metabolic profile, adherence to the mediterranean diet, and body composition. Nutrients. 2021. 13. | Outcome; Comparator
47 | Basu, A, Feng, D, Planinic, P, Ebersole, JL, Lyons, TJ, Alexander, JM. Dietary Blueberry and Soluble Fiber Supplementation Reduces Risk of Gestational Diabetes in Women with Obesity in a Randomized Controlled Trial. The Journal of nutrition. 2021. 151:1128. | Intervention/Exposure
48 | Basu, A, Alman, AC, Snell-Bergeon, JK. Associations of Dietary Patterns and Nutrients with Glycated Hemoglobin in Participants with and without Type 1 Diabetes. Nutrients. 2021. 13. doi:10.3390/nu13031035 | Outcome
49 | Beasley, JeannetteM, Yi, StellaS, Ahn, Jiyoung, Kwon, SimonaC, Wylie-Rosett, Judith. Dietary Patterns in Chinese Americans are Associated with Cardiovascular Disease Risk Factors, the Chinese American Cardiovascular Health Assessment (CHA CHA). Journal of Immigrant & Minority Health. 2019. 21:1061-1069. doi:10.1007/s10903-018-0800-z | Study Design
50 | Becerra-Tomás, N, Díaz-López, A, Rosique-Esteban, N, et al. Legume consumption is inversely associated with type 2 diabetes incidence in adults: A prospective assessment from the PREDIMED study. Clinical Nutrition. 2018. 37:906. | Intervention/Exposure
51 | Beltaief, K, Bouida, W, Trabelsi, I, Baccouche, H, Sassi, M, Dridi, Z, Chakroun, T, Hellara, I, Boukef, R, Hassine, M, Addad, F, Razgallah, R, Khochtali, I, Nouira, S. Metabolic effects of ramadan fasting in patients at high risk of cardiovascular diseases. International Journal of General Medicine. 2019. 12:247-254. doi:10.2147/IJGM.S172341 | Study Design; Intervention/Exposure
52 | Ben-Yacov O, Godneva A, Rein M, Shilo S, Kolobkov D, Koren N, Cohen Dolev N, Travinsky Shmul T, Wolf BC, Kosower N, Sagiv K, Lotan-Pompan M, Zmora N, Weinberger A, Elinav E, Segal E. Personalized Postprandial Glucose Response-Targeting Diet Versus Mediterranean Diet for Glycemic Control in Prediabetes. 44. | Intervention/Exposure
53 | Bergia, RE, Giacco, R, Hjorth, T, Biskup, I, Zhu, W, Costabile, G, Vitale, M, Campbell, WW, Landberg, R, Riccardi, G. Differential Glycemic Effects of Low-versus High-Glycemic Index Mediterranean-Style Eating Patterns in Adults at Risk for Type 2 Diabetes: The MEDGI-Carb Randomized Controlled Trial. Nutrients. 2022. 14. | Intervention/Exposure; Comparator
54 | Bhupathiraju SN, Sawicki CM, Goon S, Gujral UP, Hu FB, Kandula NR, Kanaya AM. A healthy plant-based diet is favorably associated with cardiometabolic risk factors among participants of South Asian ancestry. | Size of Study Groups
55 | Bianco A, Franco I, Curci R, Bonfiglio C, Campanella A, Mirizzi A, Fucilli F, Di Giovanni G, Giampaolo N, Pesole PL, Osella AR. Diet and Exercise Exert a Differential Effect on Glucose Metabolism Markers According to the Degree of NAFLD Severity. 15. | Health Status
56 | Blancas-Sánchez IM, Del Rosal Jurado M, Aparicio-Martínez P, Quintana Navarro G, Vaquero-Abellan M, Castro Jiménez RA, Fonseca Pozo FJ. A Mediterranean-Diet-Based Nutritional Intervention for Children with Prediabetes in a Rural Town: A Pilot Randomized Controlled Trial. 14. | Size of Study Groups
57 | Bogataj Jontez N, Kenig S, Šik Novak K, Petelin A, Jenko Pražnikar Z, Mohorko N. Habitual low carbohydrate high fat diet compared with omnivorous, vegan, and vegetarian diets. 10. | Study Design
58 | Bonaccio, M, Di Castelnuovo, A, Costanzo, S, De Curtis, A, Persichillo, M, Cerletti, C, Donati, MB, de Gaetano, G, Iacoviello, L, de Gaetano, G, Bonaccio, M, Bonanni, A, De Curtis, A, de Gaetano, G, Di Castelnuovo, A, Donati, MB, Di Prospero, T, Vermylen, J, De Paula Carrasco, I, Giampaoli, S, Spagnuolo, A, Assanelli, D, Centritto, V, Olivieri, M, Olivieri, M, Di Castelnuovo, A, Bonaccio, M, Gialluisi, A, Ruggiero, E, De Curtis, A, Magnacca, S, Izzi, B, Marotta, A, Noro, F, Bonanni, A, De Lucia, F, Gianfagna, F, Bracone, F, De Lucia, F, Dudiez, S, Rago, L, Rago, L, De Curtis, A, Panzera, T. Association of a traditional Mediterranean diet and non-Mediterranean dietary scores with all-cause and cause-specific mortality: prospective findings from the Moli-sani Study. European Journal of Nutrition. 2021. 60:729-746. doi:10.1007/s00394-020-02272-7 | Outcome
59 | Bonaccio, M, Di Castelnuovo, A, Costanzo, S, De Curtis, A, Persichillo, M, Cerletti, C, Donati, MB, de Gaetano, G, Iacoviello, L. Impact of combined healthy lifestyle factors on survival in an adult general population and in high-risk groups: prospective results from the Moli-sani Study. Journal of Internal Medicine. 2019. 286:207-220. doi:10.1111/joim.12907 | Outcome; Comparator
60 | Borgen, I, Smastuen, MC, Jacobsen, AF, Garnweidner-Holme, LM, Fayyad, S, Noll, J, Lukasse, M. Effect of the Pregnant+ smartphone application in women with gestational diabetes mellitus: a randomised controlled trial in Norway. BMJ Open. 2019. 9:e030884. doi:10.1136/bmjopen-2019-030884 | Study Design; Intervention/Exposure
61 | Bozkuş, Y, Mousa, U, Demir, CC, Anil, C, Kut, A, Iyidir, OT, Kirnap, NG, Fırat, S, Nar, A, Tutuncu, NB. Abdominal bioelectric impedance for follow-up of dieters: A prospective study. Acta Endocrinologica. 2019. 15:145-152. doi:10.4183/aeb.2019.145 | Study Design; Intervention/Exposure
62 | Brady, EmerM, Gulsin, GauravS, Mirkes, EvgenyM, Parke, Kelly, Kanagala, Prathap, Ng, LeongL, Graham-Brown, MatthewPM, Athithan, Lavanya, Henson, Joseph, Redman, Emma, Yang, Jang, Zhao, Lei, Argyridou, Stavroula, Gray, LauraJ, Yates, Thomas, Davies, MelanieJ, McCann, GerryP. Fibro-inflammatory recovery and type 2 diabetes remission following a low calorie diet but not exercise training: A secondary analysis of the DIASTOLIC randomised controlled trial. Diabetic Medicine. 2022. 39:1-11. doi:10.1111/dme.14884 | Study Design; Intervention/Exposure; Health Status
63 | Brand, C, Martins, CML, Lemes, VB, Pessoa, MLF, Dias, AF, Cadore, EL, Mota, J, Gaya, ACA, Gaya, AR. Effects and prevalence of responders after a multicomponent intervention on cardiometabolic risk factors in children and adolescents with overweight/obesity: Action for health study. J Sports Sci. 2020. 38:682-691. doi:10.1080/02640414.2020.1725384 | Intervention/Exposure
64 | Brinkworth, GD, Wycherley, TP, Taylor, PJ, Thompson, CH. A Health Care Professional Delivered Low Carbohydrate Diet Program Reduces Body Weight, Haemoglobin A1c, Diabetes Medication Use and Cardiovascular Risk Markers—A Single-Arm Intervention Analysis. Nutrients. 2022. 14. | Study Design; Intervention/Exposure
65 | Broś-Konopielko, M, Białek, A, Oleszczuk-Modzelewska, L, Zaleśkiewicz, B, Różańska-Walędziak, A, Czajkowski, K. Nutritional, anthropometric and sociodemographic factors affecting fatty acids profile of pregnant women’s serum at labour—chemometric studies. Nutrients. 2021. 13. doi:10.3390/nu13092948 | Intervention/Exposure; Outcome
66 | Buchman, M, Jin, Q, Sotos-Prieto, M. The effectiveness of the Healthy Heart Score Intervention as a Primordial Prevention Tool in a Primary Care Setting: a Randomized Controlled Trial, Pilot Study. Revista espanola de nutricion humana y dietetica. 2019. 23:204-205. | Publication Status
67 | Buckland, G, Northstone, K, Emmett, PM, Taylor, CM. The inflammatory potential of the diet in childhood is associated with cardiometabolic risk in adolescence/young adulthood in the ALSPAC birth cohort. European Journal of Nutrition. 2022. 61:3471. | Intervention/Exposure
68 | Bulunç, NH, Yıldız, E. The Relationship between Biochemical and Hemoglobin Results and Quality Index Scores of the Mediterranean Diet of Pregnant Women in the First and the Third Trimester. Progress in Nutrition. 2021. 23. | Study Design
69 | Caferoglu, Z, Erdal, B, Hatipoglu, N, Kurtoglu, S. The effects of diet quality and dietary acid load on insulin resistance in overweight children and adolescents. Los efectos de la calidad de la dieta y la carga ácida de la dieta sobre la resistencia a la insulina en niños y adolescentes con sobrepeso. 2022. | Study Design
70 | Cai, J, Zhang, Y, Nuli, R, Zhang, Y, Abudusemaiti, M, Kadeer, A, Tian, X, Xiao, H. Interaction between dietary patterns and TCF7L2 polymorphisms on type 2 diabetes mellitus among uyghur adults in Xinjiang province, China. Diabetes, Metabolic Syndrome and Obesity: Targets and Therapy. 2019. 12:239-255. doi:10.2147/DMSO.S191759 | Study Design
71 | Cai, L, Yin, J, Ma, X, Mo, Y, Li, C, Lu, W, Bao, Y, Zhou, J, Jia, W. Low-carbohydrate diets lead to greater weight loss and better glucose homeostasis than exercise: a randomized clinical trial. Frontiers of medicine. 2021. 15:460-471. doi:10.1007/s11684-021-0861-6 | Intervention/Exposure; Study Duration
72 | Cai, Q, Dekker, LH, Vinke, PC, Corpeleijn, E, Bakker, SJL, de Borst, MH, Navis, GJ. Diet quality and incident chronic kidney disease in the general population: The Lifelines Cohort Study. Clinical Nutrition. 2021. 40:5099. | Outcome
73 | Calabrese, FM, Disciglio, V, Franco, I, Sorino, P, Bonfiglio, C, Bianco, A, Campanella, A, Lippolis, T, Pesole, PL, Polignano, M, Vacca, M, Caponio, GR, Giannelli, G, De Angelis, M, Osella, AR. A Low Glycemic Index Mediterranean Diet Combined with Aerobic Physical Activity Rearranges the Gut Microbiota Signature in NAFLD Patients. Nutrients. 2022. 14. | Intervention/Exposure; Health Status
74 | Calvo-Malvar, Mar, Benítez-Estévez, AlfonsoJ, Leis, Rosaura, Sánchez-Castro, Juan, Gude, Francisco. Changes in Dietary Patterns through a Nutritional Intervention with a Traditional Atlantic Diet: The Galiat Randomized Controlled Trial. Nutrients. 2021. 13:4233-4233. doi:10.3390/nu13124233 | Outcome
75 | Camargo, A, Vals-Delgado, C, Alcala-Diaz, JF, Villasanta-Gonzalez, A, Gomez-Delgado, F, Haro, C, Leon-Acuna, A, Cardelo, MP, Torres-Pena, JD, Guler, I, Malagon, MM, Ordovas, JM, Perez-Martinez, P, Delgado-Lista, J, Lopez-Miranda, J. A Diet-Dependent Microbiota Profile Associated with Incident Type 2 Diabetes: From the CORDIOPREV Study. Mol Nutr Food Res. 2020. e2000730. doi:10.1002/mnfr.202000730 | Intervention/Exposure
76 | Cani, PD, Van Hul, M. Do diet and microbes really ‘PREDICT’ cardiometabolic risks?. Nature Reviews Endocrinology. 2021. 17:259. | Study Design
77 | Cao, Y, Chen, C, Cui, L, Han, A, Tu, Q, Lou, P, Ding, G, Qin, Y, Xiang, Q. A population-based survey for dietary patterns and prediabetes among 7555 Chinese adults in urban and rural areas in Jiangsu Province. Sci Rep. 2020. 10:10488. doi:10.1038/s41598-020-67028-z | Study Design
78 | Capurso, Antonio, Capurso, Cristiano. The Mediterranean way: why elderly people should eat wholewheat sourdough bread—a little known component of the Mediterranean diet and healthy food for elderly adults. Aging Clinical & Experimental Research. 2020. 32:1-5. doi:10.1007/s40520-019-01392-3 | Study Design; Publication Status
79 | Carballo-Casla, A, Ortola, R, Garcia-Esquinas, E, Oliveira, A, Sotos-Prieto, M, Lopes, C, Lopez-Garcia, E, Rodriguez-Artalejo, F. The Southern European Atlantic Diet and all-cause mortality in older adults. BMC Med. 2021. 19:36. doi:10.1186/s12916-021-01911-y | Outcome
80 | Carson, AP, Long, DL, Cherrington, AL, Dutton, GR, Howard, VJ, Brown, TM, Howard, G, Safford, MM, Cushman, M. Sex Differences in Factors Contributing to the Racial Disparity in Diabetes Risk. Am J Prev Med. 2021. 60:e169-e177. doi:10.1016/j.amepre.2020.09.016 | Intervention/Exposure; Comparator
81 | Castro-Juarez, AA, Serna-Gutiérrez, A, Alemán-Mateo, H, Gallegos-Aguilar, AC, Dórame-López, NA, Valenzuela-Sánchez, A, Valenzuela-Guzmán, DM, Díaz-Zavala, RG, Urquidez-Romero, R, Esparza-Romero, J. Effectiveness of a Lifestyle Change Program on Insulin Resistance in Yaquis Indigenous Populations in Sonora, Mexico: PREVISY. Nutrients. 2023. 15. | Intervention/Exposure
82 | Ceraudo F, Caparello G, Galluccio A, Avolio E, Augimeri G, De Rose D, Vivacqua A, Morelli C, Barone I, Catalano S, Giordano C, Sisci D, Bonofiglio D. Impact of Mediterranean Diet Food Choices and Physical Activity on Serum Metabolic Profile in Healthy Adolescents: Findings from the DIMENU Project. 14. | Study Design; Intervention/Exposure
83 | Cha E, Pasquel FJ, Yan F, Jacobs DR Jr, Dunbar SB, Umpierrez G, Choi Y, Shikany JM, Bancks MP, Reis JP, Spezia Faulkner M. Characteristics associated with early- vs. later-onset adult diabetes: the CARDIA study. | Size of Study Groups
84 | Chelu, S, Bernad, E, Craina, M, Neamtu, R, Mocanu, AG, Vernic, C, Chiriac, VD, Tomescu, L, Borza, C. Prevalence of Gestational Diabetes in preCOVID-19 and COVID-19 Years and Its Impact on Pregnancy: A 5-Year Retrospective Study. Diagnostics. 2022. 12. | Intervention/Exposure
85 | Chen B, Zeng J, Qin M, Xu W, Zhang Z, Li X, Xu S. The Association Between Plant-Based Diet Indices and Obesity and Metabolic Diseases in Chinese Adults: Longitudinal Analyses From the China Health and Nutrition Survey. 9. | Country
86 | Chen GC, Chai JC, Xing J, Moon JY, Shan Z, Yu B, Mossavar-Rahman Y, Sotres-Alvarez D, Li J, Mattei J, Daviglus ML, Perkins DL, Burk RD, Boerwinkle E, Kaplan RC, Hu FB, Qi Q. Healthful eating patterns, serum metabolite profile and risk of diabetes in a population-based prospective study of US Hispanics/Latinos. | Intervention/Exposure; Comparator
87 | Chen Y, Qin Y, Zhang Z, Huang S, Jiao C, Zhang Z, Bao W, Mao L. Association of the low-carbohydrate dietary pattern with postpartum weight retention in women. | Intervention/Exposure
88 | Chen Z, Qian F, Liu G, Li M, Voortman T, Tobias DK, Ley SH, Bhupathiraju SN, Li LJ, Chavarro JE, Sun Q, Hu FB, Zhang C. Prepregnancy plant-based diets and the risk of gestational diabetes mellitus: a prospective cohort study of 14,926 women. | Life Stage
89 | Chen, Q, Chen, Y, Wu, W, Tang, N, Wang, D, Chen, Y, Jing, J, Cai, L. Low-carbohydrate diet and maternal glucose metabolism in Chinese pregnant women. Br J Nutr. 2021. 126:392-400. doi:10.1017/S0007114520004092 | Intervention/Exposure; Outcome
90 | Chen, Q, Feng, Y, Yang, H, Wu, W, Zhang, P, Wang, K, Wang, Y, Ko, J, Shen, J, Guo, L, Zhao, F, Du, W, Ru, S, Wang, S, Zhang, Y. A vitamin pattern diet is associated with decreased risk of gestational diabetes mellitus in Chinese women: Results from a case control study in Taiyuan, China. Journal of Diabetes Research. 2019. 2019. doi:10.1155/2019/5232308 | Study Design
91 | Chen, Q, Wu, W, Yang, H, Zhang, P, Feng, Y, Wang, K, Wang, Y, Wang, S, Zhang, Y. A Vegetable Dietary Pattern Is Associated with Lowered Risk of Gestational Diabetes Mellitus in Chinese Women. Diabetes Metab J. 2020. 44:887-896. doi:10.4093/dmj.2019.0138 | Study Design
92 | Chen, X, Su, H, Kunii, D, Kudou, K, Zhang, Y, Zhao, Y, Zhang, D, Xing, Y, Teng, J, Nie, Z, Liu, X, Niu, K, Zhao, Y, Guo, Q. The Effects of Mobile-App-Based Low-Carbohydrate Dietary Guidance on Postprandial Hyperglycemia in Adults with Prediabetes. Diabetes Therapy. 2020. 11:2341-2355. doi:10.1007/s13300-020-00906-x | Intervention/Exposure
93 | Chen, Y, Zhou, T, Sun, D, Li, X, Ma, H, Liang, Z, Heianza, Y, Pei, X, Bray, GA, Sacks, FM, Qi, L. Distinct genetic subtypes of adiposity and glycemic changes in response to weight-loss diet intervention: the POUNDS Lost trial. European Journal of Nutrition. 2021. 60:249-258. doi:10.1007/s00394-020-02244-x | Intervention/Exposure
94 | Chen, Zhangling, Franco, OscarH, Lamballais, Sander, Ikram, Arfan M, Schoufour, JosjeD, Muka, Taulant, Voortman, Trudy. Associations of specific dietary protein with longitudinal insulin resistance, prediabetes and type 2 diabetes: The Rotterdam Study. Clinical Nutrition. 2020. 39:242-249. doi:10.1016/j.clnu.2019.01.021 | Intervention/Exposure
95 | Chen, Zhangling, Qian, Frank, Liu, Gang, Li, Mengying, Voortman, Trudy, Ley, SylviaH, Chavarro, JorgeE, Bhupathiraju, Shilpa, Sun, QI, Hu, Frank, Zhang, Cuilin. 189-OR: Prepregnancy Plant-Based Diet and the Risk of Gestational Diabetes Mellitus: A Prospective Cohort Study of 15,999 Women. Diabetes. 2020. 69. doi:10.2337/db20-189-OR | Study Design; Publication Status
96 | Chevli, PA, Mehta, A, Allison, M, Ding, J, Nasir, K, Blaha, MJ, Blankstein, R, Talegawkar, SA, Kanaya, AM, Shapiro, MD, Mongraw-Chaffin, M. Relationship of American Heart Association’s Life Simple 7, Ectopic Fat, and Insulin Resistance in 5 Racial/Ethnic Groups. Journal of Clinical Endocrinology and Metabolism. 2022. 107:E2394. | Study Design; Intervention/Exposure
97 | Choi, BG, Dhawan, T, Metzger, K, Marshall, L, Akbar, A, Jain, T, Young, HA, Katz, RJ. Image-Based Mobile System for Dietary Management in an American Cardiology Population: pilot Randomized Controlled Trial to Assess the Efficacy of Dietary Coaching Delivered via a Smartphone App Versus Traditional Counseling. JMIR mhealth and uhealth. 2019. 7:e10755. doi:10.2196/10755 | Intervention/Exposure; Comparator
98 | Choudhary, P, Ronkainen, J, Nedelec, R, Tolvanen, M, Lowry, E, Miettunen, J, Jarvelin, M-R, Sebert, S. The relationship of life-course patterns of adiposity with type 2 diabetes, depression, and their comorbidity in the Northern Finland Birth Cohort 1966. International journal of obesity (2005). 2022. | Intervention/Exposure
99 | Christensen, L, Thorning, TK, Fabre, O, Legrand, R, Astrup, A, Hjorth, MF. Metabolic improvements during weight loss: The RNPC® cohort. Obesity Medicine. 2019. 14. doi:10.1016/j.obmed.2019.100085 | Study Design
100 | Chung, S, Kim, MS, Kwock, CK. Dietary patterns may be nonproportional hazards for the incidence of type 2 diabetes: Evidence from Korean adult females. Nutrients. 2019. 11. doi:10.3390/nu11102522 | Comparator
101 | Cipryan L, Litschmannova M, Maffetone PB, Plews DJ, Dostal T, Hofmann P, Laursen PB. Very Low-Carbohydrate High-Fat Diet Improves Risk Markers for Cardiometabolic Health More Than Exercise in Men and Women With Overfat Constitution: Secondary Analysis of a Randomized Controlled Clinical Trial. 9. | Intervention/Exposure
102 | Cipryan, L, Dostal, T, Plews, DJ, Hofmann, P, Laursen, PB. Adiponectin/leptin ratio increases after a 12-week very low-carbohydrate, high-fat diet, and exercise training in healthy individuals: A non-randomized, parallel design study. Nutr Res. 2021. 87:22-30. doi:10.1016/j.nutres.2020.12.012 | Intervention/Exposure
103 | Clemente, G, Giorgini, M, Della Pia, N, Cerbara, L, Liuzzi, R, Cipriano, P, Riccardi, G, Vaccaro, O. Effectiveness on major cardiovascular risk factors of an educational program to promote a Mediterranean type of diet among the employees of the company FCA Italia S.p.A. Diabetes Res Clin Pract. 2021. 179:109009. doi:10.1016/j.diabres.2021.109009 | Intervention/Exposure; Comparator
104 | Cobos-Palacios L, Ruiz-Moreno MI, Vilches-Perez A, Vargas-Candela A, Muñoz-Úbeda M, Benítez Porres J, Navarro-Sanz A, Lopez-Carmona MD, Sanz-Canovas J, Perez-Belmonte LM, Mancebo-Sevilla JJ, Gomez-Huelgas R, Bernal-Lopez MR. Metabolically healthy obesity: Inflammatory biomarkers and adipokines in elderly population. 17. | Study Design; Intervention/Exposure; Outcome
105 | Cockerham WC, Bauldry S, Sims M. Obesity-Related Health Lifestyles of Late-Middle Age Black Americans: The Jackson Heart Study. 63. | Study Design; Intervention/Exposure
106 | Cockroft, Marianne Channas, Bartlett, Robin T, Wallace, DebraC. Sleep, Nutrition, Disordered Eating, Problematic Tobacco and Alcohol Use, and Exercise in College Students With and Without Diabetes. Journal of Psychosocial Nursing & Mental Health Services. 2019. 57:23-32. doi:10.3928/02793695-20190919-04 | Study Design; Intervention/Exposure
107 | Comas Rovira M, Moreno Baró A, Burgaya Guiu N, Toledo Mesa L, Lesmes Heredia C, Pina Pérez S, Grimau Gallego M, Martí Malgosa L, Cochs Cosme B, Costa Pueyo J. The influence of obesity and diet quality on fetal growth and perinatal outcome. | Confounders
108 | Corsi Decenti E, Zambri F, Salvatore MA, Lacaria E, Chellini M, Grillo A, Denoth F, Franchini M, Molinaro S, Ghio A, Bini L, Gregori G, Mori M, Di Cianni G. Dietary habits, lifestyle, and gestational diabetes in immigrant women: a survey in Northwestern Tuscany (Central Italy). 46. | Study Design; Comparator
109 | Costa-Urrutia, P, Alvarez-Farina, R, Abud, C, Franco-Trecu, V, Esparza-Romero, J, Lopez-Morales, CM, Rodriguez-Arellano, ME, Valle Leal, J, Colistro, V, Granados, J. Effect of multi-component school-based program on body mass index, cardiovascular and diabetes risks in a multi-ethnic study. BMC Pediatr. 2019. 19:401. doi:10.1186/s12887-019-1787-x | Intervention/Exposure
110 | Costello E, Goodrich J, Patterson WB, Rock S, Li Y, Baumert B, Gilliland F, Goran MI, Chen Z, Alderete TL, Conti DV, Chatzi L. Diet Quality Is Associated with Glucose Regulation in a Cohort of Young Adults. 14. | Size of Study Groups
111 | Courten, Barbora De, Karim, Md Nazmul, Hodge, Allison. 714-P: Dietary Pattern and Risk of Type 2 Diabetes In Melbourne Collaborative Cohort. Diabetes. 2020. 69. doi:10.2337/db20-714-P | Publication Status
112 | Crimarco, A, Springfield, S, Petlura, C, Streaty, T, Cunanan, K, Lee, J, Fielding-Singh, P, Carter, MM, Topf, MA, Wastyk, HC, Sonnenburg, ED, Sonnenburg, JL, Gardner, CD. A randomized crossover trial on the effect of plant-based compared with animal-based meat on trimethylamine-N-oxide and cardiovascular disease risk factors in generally healthy adults: Study With Appetizing Plantfood-Meat Eating Alternative Trial (SWAP-MEAT). Am J Clin Nutr. 2020. 112:1188-1199. doi:10.1093/ajcn/nqaa203 | Intervention/Exposure; Study Duration
113 | Croxford, S, Gupta, D, Bandyopadhyay, M, Itsiopoulos, C. An evaluation of dietary intakes of a selected group of South Asian migrant women with gestational diabetes mellitus. Ethn Health. 2021. 26:487-503. doi:10.1080/13557858.2018.1539217 | Study Design; Outcome
114 | Cuesta, M, Fuentes, M, Rubio, M, Bordiu, E, Barabash, A, Garcia de la Torre, N, Rojo-Martinez, G, Valdes, S, Soriguer, F, Vendrell, JJ, Urrutia, IM, Ortega, E, Montanya, E, Menendez, E, Lago-Sampedro, A, Gomis, R, Goday, A, Castell, C, Badia-Guillen, R, Girbes, J, Gaztambide, S, Franch-Nadal, J, Delgado Alvarez, E, Chaves, FJ, Castano, L, Calle-Pascual, AL. Incidence and regression of metabolic syndrome in a representative sample of the Spanish population: results of the cohort di@bet.es study. BMJ Open Diabetes Res Care. 2020. 8. doi:10.1136/bmjdrc-2020-001715 | Outcome
115 | Curci R, Bianco A, Franco I, Campanella A, Mirizzi A, Bonfiglio C, Sorino P, Fucilli F, Di Giovanni G, Giampaolo N, Pesole PL, Osella AR. The Effect of Low Glycemic Index Mediterranean Diet and Combined Exercise Program on Metabolic-Associated Fatty Liver Disease: A Joint Modeling Approach. 11. | Study Design; Intervention/Exposure
116 | Currenti, W, Godos, J, Alanazi, AM, Grosso, G, Cincione, RI, La Vignera, S, Buscemi, S, Galvano, F. Dietary Fats and Cardio-Metabolic Outcomes in a Cohort of Italian Adults. Nutrients. 2022. 14. | Study Design; Intervention/Exposure
117 | Cyr-Scully A, Howard AG, Sanzone E, Meyer KA, Du S, Zhang B, Wang H, Gordon-Larsen P. Characterizing the urban diet: development of an urbanized diet index. 21. | Study Design
118 | Czekajło, A, Różańska, D, Zatońska, K, Szuba, A, Regulska-Ilow, B. Association between dietary patterns and metabolic syndrome in the selected population of Polish adults-results of the PURE Poland Study. European journal of public health. 2019. 29:335-340. doi:10.1093/eurpub/cky207 | Study Design
119 | Czekajlo-Kozlowska, A, Rozanska, D, Zatonska, K, Szuba, A, Regulska-Ilow, B. Association between egg consumption and elevated fasting glucose prevalence in relation to dietary patterns in selected group of Polish adults. Nutr J. 2019. 18:90. doi:10.1186/s12937-019-0516-5 | Intervention/Exposure; Outcome
120 | Das, SK, Bukhari, AS, Taetzsch, AG, Ernst, AK, Rogers, GT, Gilhooly, CH, Hatch-Mcchesney, A, Blanchard, CM, Livingston, KA, Silver, RE, Martin, E, McGraw, SM, Chin, MK, Vail, TA, Lutz, LJ, Montain, SJ, Pittas, AG, Lichtenstein, AH, Allison, DB, Dickinson, S, Chen, X, Saltzman, E, Young, AJ, Roberts, SB. Randomized trial of a novel lifestyle intervention compared with the Diabetes Prevention Program for weight loss in adult dependents of military service members. American Journal of Clinical Nutrition. 2021. 114:1546. | Intervention/Exposure
121 | De Giuseppe, R, Bocchi, M, Maffoni, S, Del Bo, E, Manzoni, F, Cerbo, RM, Porri, D, Cena, H. Mediterranean diet and lifestyle habits during pregnancy: Is there an association with small for gestational age infants? an italian single centre experience. Nutrients. 2021. 13. | Study Design; Outcome
122 | De La Torre, NG, Assaf-Balut, C, Varas, IJ, Del Valle, L, Durán, A, Fuentes, M, Del Prado, N, Bordiú, E, Valerio, JJ, Herraiz, MA, Izquierdo, N, Torrejón, MJ, Cuadrado, MA, De Miguel, P, Familiar, C, Runkle, I, Barabash, A, Rubio, MA, Calle-Pascual, AL. Effectiveness of following mediterranean diet recommendations in the real world in the incidence of gestational diabetes mellitus (Gdm) and adverse maternal-foetal outcomes: A prospective, universal, interventional study with a single group. the st carlos study. Nutrients. 2019. 11. doi:10.3390/nu11061210 | Study Design
123 | de Luis, D, Izaola, O, Primo, D. APOA-5 Genetic Variant rs662799: Role in Lipid Changes and Insulin Resistance after a Mediterranean Diet in Caucasian Obese Subjects. Dis Markers. 2021. 2021:1257145. doi:10.1155/2021/1257145 | Intervention/Exposure; Comparator
124 | de Luis, DA, Izaola, O, Primo, D, Aller, R. Dietary-fat effect of the rs10830963 polymorphism in MTNR1B on insulin resistance in response to 3 months weight-loss diets. Endocrinol Diabetes Nutr (Engl Ed). 2020. 67:43-52. doi:10.1016/j.endinu.2019.02.007 | Intervention/Exposure
125 | de Luis, DA, Izaola, O, Primo, D, Aller, R. Different effects of high-protein/low-carbohydrate versus standard hypocaloric diet on insulin resistance and lipid profile: Role of rs16147 variant of neuropeptide Y. Diabetes Research and Clinical Practice. 2019. 156. doi:10.1016/j.diabres.2019.107825 | Intervention/Exposure; Comparator
126 | de Luis, DA, Izaola, O, Primo, D, Gómez-Hoyos, E, Ortola, A, López-Gómez, JJ, Aller, R. Role of rs1501299 variant in the adiponectin gene on total adiponectin levels, insulin resistance and weight loss after a Mediterranean hypocaloric diet. Diabetes Research and Clinical Practice. 2019. 148:262-267. doi:10.1016/j.diabres.2017.11.007 | Study Design; Intervention/Exposure
127 | de Luis, DA, Primo, D, Izaola, O, Aller, R. Adiponectin Gene Variant rs266729 Interacts with Different Macronutrient Distribution of Two Different Hypocaloric Diets. Lifestyle Genom. 2020. 13:20-27. doi:10.1159/000503863 | Intervention/Exposure
128 | de Luis, DA, Primo, D, Izaola, O, Gomez Hoyos, E, Lopez Gomez, JJ, Ortola, A, Aller, R. Role of the variant in adiponectin gene rs266729 on weight loss and cardiovascular risk factors after a hypocaloric diet with the Mediterranean pattern. Nutrition. 2019. 60:1-5. doi:10.1016/j.nut.2018.08.018 | Study Design; Intervention/Exposure
129 | de Luis, DA, Primo, D, Izaola, O, Gomez, E, Bachiller, R. Serum Lipid and Adiponectin Improvements after a Mediterranean Dietary Pattern in Non-G-Allele Carriers of the Variant rs3774261. Lifestyle Genom. 2020. 13:164-171. doi:10.1159/000508819 | Study Design; Intervention/Exposure
130 | De Pergola, G, Zupo, R, Lampignano, L, Bonfiglio, C, Giannelli, G, Osella, AR, Triggiani, V. Higher Body Mass Index, Uric Acid Levels, and Lower Cholesterol Levels are Associated with Greater Weight Loss. Endocr Metab Immune Disord Drug Targets. 2020. 20:1268-1281. doi:10.2174/1871530320666200429235830 | Study Design; Intervention/Exposure
131 | Deledda A, Palmas V, Heidrich V, Fosci M, Lombardo M, Cambarau G, Lai A, Melis M, Loi E, Loviselli A, Manzin A, Velluzzi F. Dynamics of Gut Microbiota and Clinical Variables after Ketogenic and Mediterranean Diets in Drug-Naïve Patients with Type 2 Diabetes Mellitus and Obesity. 12. | Health Status
132 | Deng, Xiangling, Niu, Wenquan. Plant-Based Dietary Patterns and Incidence of Type 2 Diabetes. 2019. 179:1603-1604. doi:10.1001/jamainternmed.2019.4860 | Study Design; Publication Status
133 | Desormeaux, Genevieve, Petrick, HeatherL, Brunetta, Henver, Holloway, Graham. 1805-P: Dietary Nitrate Prevents High-Fat Diet-Induced Glucose Intolerance and Liver-Specific Reactive Oxygen Species Emission. Diabetes. 2020. 69. doi:10.2337/db20-1805-P | Publication Status
134 | di Giuseppe, R, Plachta-Danielzik, S, Koch, M, Nöthlings, U, Schlesinger, S, Borggrefe, J, Both, M, Müller, HP, Kassubek, J, Jacobs, G, Lieb, W. Dietary pattern associated with selenoprotein P and MRI-derived body fat volumes, liver signal intensity, and metabolic disorders. European Journal of Nutrition. 2019. 58:1067-1079. doi:10.1007/s00394-018-1624-2 | Study Design
135 | Dodd, JM, Deussen, AR, Louise, J. A Randomised Trial to Optimise Gestational Weight Gain and Improve Maternal and Infant Health Outcomes through Antenatal Dietary, Lifestyle and Exercise Advice: The OPTIMISE Randomised Trial. Nutrients. 2019. 11. doi:10.3390/nu11122911 | Intervention/Exposure
136 | Domínguez-Coello, Santiago, Carrillo-Fernández, Lourdes, Gobierno-Hernández, Jesús, Méndez-Abad, Manuel, Borges-Álamo, Carlos, García-Dopico, José Antonio, Aguirre-Jaime, Armando, Cabrera-de León, Antonio. Decreased Consumption of Added Fructose Reduces Waist Circumference and Blood Glucose Concentration in Patients with Overweight and Obesity. The DISFRUTE Study: A Randomised Trial in Primary Care. Nutrients. 2020. 12:1149-1149. doi:10.3390/nu12041149 | Intervention/Exposure
137 | Dong, H, Sun, H, Cai, C, Pang, X, Bai, D, Lan, X, Zhang, Y, Zhang, J, Zeng, G. A low-carbohydrate dietary pattern characterised by high animal fat and protein during the first trimester is associated with an increased risk of gestational diabetes mellitus in Chinese women: a prospective cohort study. Br J Nutr. 2021. 1-9. doi:10.1017/S0007114521000611 | Intervention/Exposure
138 | Dorans KS, Bazzano LA, Qi L, He H, Chen J, Appel LJ, Chen CS, Hsieh MH, Hu FB, Mills KT, Nguyen BT, O’Brien MJ, Samet JM, Uwaifo GI, He J. Effects of a Low-Carbohydrate Dietary Intervention on Hemoglobin A1c: A Randomized Clinical Trial. 5. | Intervention/Exposure
139 | Dorenbos, E, Drummen, M, Adam, T, Rijks, J, Winkens, B, Martinez, JA, Navas-Carretero, S, Stratton, G, Swindell, N, Stouthart, P, Mackintosh, K, McNarry, M, Tremblay, A, Fogelholm, M, Raben, A, Westerterp-Plantenga, M, Vreugdenhil, A. Effect of a high protein/low glycaemic index diet on insulin resistance in adolescents with overweight/obesity-A PREVIEW randomized clinical trial. Pediatr Obes. 2021. 16:e12702. doi:10.1111/ijpo.12702 | Intervention/Exposure; Comparator
140 | Drummen, M, Adam, TC, Macdonald, IA, Jalo, E, Larssen, TM, Martinez, JA, Handjiev-Darlenska, T, Brand-Miller, J, Poppitt, SD, Stratton, G, Pietilainen, KH, Taylor, MA, Navas-Carretero, S, Handjiev, S, Muirhead, R, Silvestre, MP, Swindell, N, Huttunen-Lenz, M, Schlicht, W, Lam, T, Sundvall, J, Raman, L, Feskens, E, Tremblay, A, Raben, A, Westerterp-Plantenga, MS. Associations of changes in reported and estimated protein and energy intake with changes in insulin resistance, glycated hemoglobin, and BMI during the PREVIEW lifestyle intervention study. Am J Clin Nutr. 2021. doi:10.1093/ajcn/nqab247 | Intervention/Exposure; Comparator
141 | Du, M, Liu, J, Han, N, Zhao, Z, Luo, S, Wang, H. Association between sleep duration in early pregnancy and risk of gestational diabetes mellitus: a prospective cohort study. Diabetes Metab. 2020. 47:101217. doi:10.1016/j.diabet.2020.101217 | Intervention/Exposure
142 | Ebbeling, CB, Knapp, A, Johnson, A, Wong, JMW, Greco, KF, Ma, C, Mora, S, Ludwig, DS. Effects of a low-carbohydrate diet on insulin-resistant dyslipoproteinemia-a randomized controlled feeding trial. The American journal of clinical nutrition. 2021. | Intervention/Exposure
143 | Effoe, VS, Carnethon, MR, Echouffo-Tcheugui, JB, Chen, H, Joseph, JJ, Norwood, AF, Bertoni, AG. The American Heart Association Ideal Cardiovascular Health and Incident Type 2 Diabetes Mellitus Among Blacks: The Jackson Heart Study. Journal of the American Heart Association. 2017. 6. | Intervention/Exposure; Outcome; Comparator
144 | Efthymiou, Vasiliki, Charmandari, Evangelia, Vlachakis, Dimitrios, Tsitsika, Artemis, Pałasz, Artur, Chrousos, George, Bacopoulou, Flora. Adolescent Self-Efficacy for Diet and Exercise Following a School-Based Multicomponent Lifestyle Intervention. Nutrients. 2022. 14:97. doi:10.3390/nu14010097 | Study Design; Intervention/Exposure; Outcome
145 | Ekuni, D, Furuta, M, Kimura, T, Toyama, N, Fukuhara, D, Uchida, Y, Sawada, N, Morita, M. Association between intensive health guidance focusing on eating quickly and metabolic syndrome in Japanese middle-aged citizens. Eat Weight Disord. 2020. 25:91-98. doi:10.1007/s40519-018-0522-1 | Intervention/Exposure
146 | Epel, E, Laraia, B, Coleman-Phox, K, Leung, C, Vieten, C, Mellin, L, Kristeller, JL, Thomas, M, Stotland, N, Bush, N, Lustig, RH, Dallman, M, Hecht, FM, Adler, N. Effects of a Mindfulness-Based Intervention on Distress, Weight Gain, and Glucose Control for Pregnant Low-Income Women: A Quasi-Experimental Trial Using the ORBIT Model. International journal of behavioral medicine. 2019. 26:461-473. doi:10.1007/s12529-019-09779-2 | Intervention/Exposure
147 | Esfandiar Z, Hosseini-Esfahani F, Mirmiran P, Azizi F. The association of dietary macronutrients composition with the incidence of type 2 diabetes, using iso-energetic substitution models: Tehran Lipid and Glucose Study. | Intervention/Exposure
148 | Esfandiar, Z, Hosseini-Esfahani, F, Mirmiran, P, Yuzbashian, E, Azizi, F. The Association of Dietary Polyphenol Intake with the Risk of Type 2 Diabetes: Tehran Lipid and Glucose Study. Diabetes Metab Syndr Obes. 2020. 13:1643-1652. doi:10.2147/DMSO.S238483 | Intervention/Exposure
149 | Eshak, ES, Iso, H, Muraki, I, Tamakoshi, A. Among the water-soluble vitamins, dietary intakes of vitamins C, B2 and folate are associated with the reduced risk of diabetes in Japanese women but not men. British Journal of Nutrition. 2019. 121:1357-1364. doi:10.1017/S000711451900062X | Intervention/Exposure
150 | Fagherazzi, S, Farias, DR, Belfort, GP, Dos Santos, K, Lima, Tsvd, Santos, MSD, Saunders, C. The impact of the DASH diet on glycaemic control and consumption of processed and ultra-processed foods in pregnant women with pre-gestational diabetes mellitus: a randomized clinical trial. British journal of nutrition. 2020. doi:10.1017/S0007114520004791 | Health Status
151 | Fagherazzi, S, Farias, DR, Belfort, GP, Dos Santos, K, Santana Vieira de Lima, T, Silva Dos Santos, M, Saunders, C. Impact of the Dietary Approaches to Stop Hypertension (DASH) diet on glycaemic control and consumption of processed and ultraprocessed foods in pregnant women with pre-gestational diabetes mellitus: a randomised clinical trial. Br J Nutr. 2021. 126:865-876. doi:10.1017/S0007114520004791 | Health Status
152 | Falkenhain, K, Locke, SR, Lowe, DA, Reitsma, NJ, Lee, T, Singer, J, Weiss, EJ, Little, JP. Keyto app and device versus WW app on weight loss and metabolic risk in adults with overweight or obesity: A randomized trial. Obesity. 2021. | Intervention/Exposure
153 | Farabi SS, Smith GI, Schweitzer GG, Stein RI, Klein S. Do lifestyle factors and quality of life differ in people with metabolically healthy and unhealthy obesity?. | Study Design
154 | Farhadnejad H, Teymoori F, Asghari G, Mokhtari E, Mirmiran P, Azizi F. The higher adherence to a healthy lifestyle score is associated with a decreased risk of type 2 diabetes in Iranian adults. 22. | Intervention/Exposure
155 | Farpour-Lambert, NJ, Martin, XE, Bucher Della Torre, S, von Haller, L, Ells, LJ, Herrmann, FR, Aggoun, Y. Effectiveness of individual and group programmes to treat obesity and reduce cardiovascular disease risk factors in pre-pubertal children. Clin Obes. 2019. 9:e12335. doi:10.1111/cob.12335 | Intervention/Exposure
156 | Feng Q, Yang M, Dong H, Sun H, Chen S, Chen C, Zhang Y, Lan X, Su D, Zeng G. Dietary fat quantity and quality in early pregnancy and risk of gestational diabetes mellitus in Chinese women: a prospective cohort study. | Intervention/Exposure
157 | Fernandez, CA, Potts, K, Bazzano, LA. Effect of ideal protein versus low-fat diet for weight loss: A randomized controlled trial. Obesity Science and Practice. 2021. | Intervention/Exposure
158 | Fernández-García, JC, Martínez-Sánchez, MA, Bernal-López, MR, Muñoz-Garach, A, Martínez-González, MA, Fitó, M, Salas-Salvadó, J, Tinahones, FJ, Ramos-Molina, B. Effect of a lifestyle intervention program with energy-restricted Mediterranean diet and exercise on the serum polyamine metabolome in individuals at high cardiovascular disease risk: A randomized clinical trial. American Journal of Clinical Nutrition. 2020. 111:975. | Comparator
159 | Fernandez-Lazaro CI, Sayon-Orea C, Toledo E, Moreno-Iribas C, Guembe MJ. Association of ideal cardiovascular health with cardiovascular events and risk advancement periods in a Mediterranean population-based cohort. 20. | Outcome
160 | Fernandez-Lazaro, CI, Toledo, E, Salas-Salvado, J, Corella, D, Fito, M, Martinez, JA, Buil-Cosiales, P. PREDIMED-Plus trial: one-year changes in the quality of dietary carbohydrate intake and concurrent changes in cardiovascular risk factors. Annals of nutrition & metabolism. 2019. 75:20-21. doi:10.1159/000501441 | Publication Status
161 | Fernández-Ruiz VE, Solé-Agustí M, Armero-Barranco D, Cauli O. Weight Loss and Improvement of Metabolic Alterations in Overweight and Obese Children Through the I(2)AO(2) Family Program: A Randomized Controlled Clinical Trial. 23. | Intervention/Exposure
162 | Flores AC, Heron C, Kim JI, Martin B, Al-Shaar L, Tucker KL, Gao X. Prospective Study of Plant-Based Dietary Patterns and Diabetes in Puerto Rican Adults. | Size of Study Groups
163 | Ford, CN, Weber, MB, Staimez, LR, Anjana, RM, Lakshmi, K, Mohan, V, Narayan, KMV, Harish, R. Dietary changes in a diabetes prevention intervention among people with prediabetes: the Diabetes Community Lifestyle Improvement Program trial. Acta Diabetologica. 2019. 56:197-209. doi:10.1007/s00592-018-1249-1 | Intervention/Exposure; Country
164 | Fu Y, Yang Y, Zhu L, Chen J, Yu N, Zhao M. Effect of dietary n-6: n-3 Poly-Unsaturated fatty acids ratio on gestational diabetes mellitus: a prospective cohort. | Intervention/Exposure
165 | Gabiola, J, Morales, D, Quizon, O, Cadiz, RI, Feliciano, K, Ruiz, RL, Aguatis, CJ, Mararac, T, Rojina, J, Garcia, A, Hedlin, H, Cullen, M, Palaniappan, L. The EffectiveNess of LIfestyle with Diet and Physical Activity Education ProGram Among Prehypertensives and Stage 1 HyperTENsives in an Urban Community Setting (ENLIGHTEN) Study. J Community Health. 2020. 45:478-487. doi:10.1007/s10900-019-00764-0 | Intervention/Exposure; Country
166 | Gabriel Da Silva, LB, Rosado, EL, De Carvalho Padilha, P, Dias, JR, Moreira, TM, De Paula, TP, De Barros, DC, Saunders, C. Food intake of women with gestational diabetes mellitus, in accordance with two methods of dietary guidance: A randomised controlled clinical trial. British Journal of Nutrition. 2019. 121:82-92. doi:10.1017/S0007114518001484 | Intervention/Exposure; Health Status
167 | Gadgil MD, Ingram KH, Appiah D, Rudd J, Whitaker KM, Bennett WL, Shikany JM, Jacobs DR Jr, Lewis CE, Gunderson EP. Prepregnancy Protein Source and BCAA Intake Are Associated with Gestational Diabetes Mellitus in the CARDIA Study. 19. | Life Stage
168 | Gadgil, MD, Kanaya, AM, Sands, C, Chekmeneva, E, Lewis, MR, Kandula, NR, Herrington, DM. Diet Patterns Are Associated with Circulating Metabolites and Lipid Profiles of South Asians in the United States. Journal of Nutrition. 2022. 152:2358. | Study Design; Outcome
169 | Gainfort, A, Delahunt, A, Killeen, SL, O’Reilly, SL, H?bert, JR, Shivappa, N, McAuliffe, FM. Energy-Adjusted Dietary Inflammatory Index in pregnancy and maternal cardiometabolic health: findings from the ROLO study. AJOG Global Reports. 2023. 3. | Intervention/Exposure
170 | Gajda, R, Raczkowska, E, Sobieszczańska, M, Noculak, Ł, Szymala-Pędzik, M, Godyla-Jabłoński, M. Diet Quality Variation among Polish Older Adults: Association with Selected Metabolic Diseases, Demographic Characteristics and Socioeconomic Status. International journal of environmental research and public health. 2023. 20. | Study Design
171 | Garbutt J, England C, Jones AG, Andrews RC, Salway R, Johnson L. Is glycaemic control associated with dietary patterns independent of weight change in people newly diagnosed with type 2 diabetes? Prospective analysis of the Early-ACTivity-In-Diabetes trial. 20. | Health Status
172 | Garbutt, JDW, England, C, Jones, AG, Andrews, RC, Johnson, L. Are changes in a low-carbohydrate, high-fat diet pattern associated with subsequent changes in HbA1c during an intensive diet and physical activity intervention?. Diabetic medicine. 2020. 37:44-. doi:10.1111/dme.14245 | Publication Status
173 | Gardner CD, Landry MJ, Perelman D, Petlura C, Durand LR, Aronica L, Crimarco A, Cunanan KM, Chang A, Dant CC, Robinson JL, Kim SH. Effect of a Ketogenic Diet versus Mediterranean Diet on HbA1c in Individuals with Prediabetes and Type 2 Diabetes Mellitus: the Interventional Keto-Med Randomized Crossover Trial. | Comparator
174 | Garnæs, KK, Elvebakk, T, Salvesen, Ø, Stafne, SN, Mørkved, S, Salvesen, KÅ, Moholdt, T. Dietary intake in early pregnancy and glycemia in late pregnancy among women with obesity. Nutrients. 2022. 14. | Intervention/Exposure
175 | Garr Barry, V, Stewart, M, Soleymani, T, Desmond, RA, Goss, AM, Gower, BA. Greater Loss of Central Adiposity from Low-Carbohydrate versus Low-Fat Diet in Middle-Aged Adults with Overweight and Obesity. Nutrients. 2021. 13. doi:10.3390/nu13020475 | Intervention/Exposure
176 | Geiker, NRW, Magkos, F, Zingenberg, H, Svare, J, Chabanova, E, Thomsen, HS, Ritz, C, Astrup, A. A high-protein low-glycemic index diet attenuates gestational weight gain in pregnant women with obesity: The “An optimized programming of healthy children” (APPROACH) randomized controlled trial. American Journal of Clinical Nutrition. 2022. 115:970. | Intervention/Exposure
177 | George, ES, Georgousopoulou, EN, Mellor, DD, Chrysohoou, C, Pitsavos, C, Panagiotakos, DB. Exploring the Path of Mediterranean Diet, Non-Alcoholic Fatty Liver Disease (NAFLD) and Inflammation towards 10-Year Cardiovascular Disease (CVD) Risk: The ATTICA Study 10-Year Follow-Up (2002–2012). Nutrients. 2022. 14. | Outcome
178 | Gepner, Y, Shelef, I, Komy, O, Cohen, N, Schwarzfuchs, D, Bril, N, Rein, M, Serfaty, D, Kenigsbuch, S, Zelicha, H, Yaskolka Meir, A, Tene, L, Bilitzky, A, Tsaban, G, Chassidim, Y, Sarusy, B, Ceglarek, U, Thiery, J, Stumvoll, M, Blüher, M, Stampfer, MJ, Rudich, A, Shai, I. The beneficial effects of Mediterranean diet over low-fat diet may be mediated by decreasing hepatic fat content. Journal of Hepatology. 2019. 71:379-388. doi:10.1016/j.jhep.2019.04.013 | Intervention/Exposure
179 | Gete, DG, Waller, M, Mishra, GD. Prepregnancy dietary patterns and risk of preterm birth and low birth weight: Findings from the Australian Longitudinal Study on Women’s Health. American Journal of Clinical Nutrition. 2020. 111:1048-1058. doi:10.1093/ajcn/nqaa057 | Outcome; Comparator
180 | Giacomello L, Bordignon S, Salm D, Donatello N, Belmonte LA, Bobinski F, Tourinho Dos Santos CF, Traebert JL, Piovezan AP, Martins DF. Effects of the application of a food processing-based classification system in obese women: A randomized controlled pilot study. | Intervention/Exposure
181 | Giardina, S, Hernández-Alonso, P, Díaz-López, A, Salas-Huetos, A, Salas-Salvadó, J, Bulló, M. Changes in circulating miRNAs in healthy overweight and obese subjects: Effect of diet composition and weight loss. Clinical Nutrition. 2019. 38:438-443. doi:10.1016/j.clnu.2017.11.014 | Intervention/Exposure
182 | Gillingham, MB, Elizondo, G, Behrend, A, Matern, D, Schoeller, DA, Harding, CO, Purnell, JQ. Higher dietary protein intake preserves lean body mass, lowers liver lipid deposition, and maintains metabolic control in participants with long-chain fatty acid oxidation disorders. Journal of Inherited Metabolic Disease. 2019. 42:857-869. doi:10.1002/jimd.12155 | Intervention/Exposure; Health Status
183 | Giontella, A, Bonafini, S, Tagetti, A, Bresadola, I, Minuz, P, Gaudino, R, Cavarzere, P, Ramaroli, DA, Marcon, D, Branz, L, Principe, LN, Antoniazzi, F, Maffeis, C, Fava, C. Relation between dietary habits, physical activity, and anthropometric and vascular parameters in children attending the primary school in the Verona South District. Nutrients. 2019. 11. doi:10.3390/nu11051070 | Study Design
184 | Goff LM, Rivas C, Moore A, Beckley-Hoelscher N, Reid F, Harding S. Healthy Eating and Active Lifestyles for Diabetes (HEAL-D), a culturally tailored self-management education and support program for type 2 diabetes in black-British adults: a randomized controlled feasibility trial. 9. | Intervention/Exposure; Health Status
185 | Goff, LM, Huang, P, Silva, MJ, Bordoli, C, Enayat, EZ, Molaodi, OR, Cassidy, A, Maynard, M, Harding, S. Associations of dietary intake with cardiometabolic risk in a multi-ethnic cohort: A longitudinal analysis of the Determinants of Adolescence, now young Adults, Social well-being and Health (DASH) study. British Journal of Nutrition. 2019. 121:1069-1079. doi:10.1017/S0007114519000291 | Intervention/Exposure
186 | Goldenshluger, A, Constantini, K, Goldstein, N, Shelef, I, Schwarzfuchs, D, Zelicha, H, Yaskolka Meir, A, Tsaban, G, Chassidim, Y, Gepner, Y. Effect of Dietary Strategies on Respiratory Quotient and Its Association with Clinical Parameters and Organ Fat Loss: A Randomized Controlled Trial. Nutrients. 2021. 13. doi:10.3390/nu13072230 | Intervention/Exposure
187 | González, CarlosA, Bonet, Catalina, Pablo, Miguel de, Sanchez, María José, Salamanca-Fernandez, Elena, Dorronsoro, Miren, Amiano, Pilar, Huerta, Jose María, Chirlaque, María Dolores, Ardanaz, Eva, Barricarte, Aurelio, Quirós, Jose Ramón, Agudo, Antonio, Ferrer, Marta Guadalupe Rivera. Greenhouse gases emissions from the diet and risk of death and chronic diseases in the EPIC-Spain cohort. European Journal of Public Health. 2021. 31:130-135. doi:10.1093/eurpub/ckaa167 | Intervention/Exposure
188 | González-Domínguez Á, Domínguez-Riscart J, Millán-Martínez M, Lechuga-Sancho AM, González-Domínguez R. Exploring the association between circulating trace elements, metabolic risk factors, and the adherence to a Mediterranean diet among children and adolescents with obesity. 10. | Study Design
189 | Gower, BA, Pearson, K, Bush, N, Shikany, JM, Howard, VJ, Cohen, CW, Tison, SE, Howard, G, Judd, S. Diet pattern may affect fasting insulin in a large sample of black and white adults. European Journal of Clinical Nutrition. 2021. 75:628. | Outcome
190 | Grammatikopoulou, MG, Nigdelis, MP, Haidich, A-B, Kyrezi, M, Ntine, H, Papaioannou, M, Mintziori, G, Bogdanos, DP, Mavromatidis, G, Goulis, DG. Diet Quality and Nutritional Risk Based on the FIGO Nutrition Checklist among Greek Pregnant Women: A Cross-Sectional Routine Antenatal Care Study. Nutrients. 2023. 15. | Study Design
191 | Grangeiro, ÉD, Trigueiro, MS, Siais, LO, Paiva, HM, Sola-Penna, M, Alves, MR, Rosado, EL. Hypocaloric diet with lower meal frequency did not affect weight loss, body composition and insulin responsiveness, but improved lipid profile: a randomized clinical trial. Food & function. 2021. 12:12594. | Intervention/Exposure; Comparator
192 | Gray ME, Bae S, Ramachandran R, Baldwin N, VanWagner LB, Jacobs DR Jr, Terry JG, Shikany JM. Dietary Patterns and Prevalent NAFLD at Year 25 from the Coronary Artery Risk Development in Young Adults (CARDIA) Study. 14. | Outcome
193 | Gray, KristyL, Clifton, PeterM, Keogh, JenniferB. The effect of intermittent energy restriction on weight loss and diabetes risk markers in women with a history of gestational diabetes: a 12-month randomized control trial. American Journal of Clinical Nutrition. 2021. 114:794-803. doi:10.1093/ajcn/nqab058 | Intervention/Exposure; Comparator
194 | Guasch-Ferre, M, Santos, JL, Martinez-Gonzalez, MA, Clish, CB, Razquin, C, Wang, D, Liang, L, Li, J, Dennis, C, Corella, D, Munoz-Bravo, C, Romaguera, D, Estruch, R, Santos-Lozano, JM, Castaner, O, Alonso-Gomez, A, Serra-Majem, L, Ros, E, Canudas, S, Asensio, EM, Fito, M, Pierce, K, Martinez, JA, Salas-Salvado, J, Toledo, E, Hu, FB, Ruiz-Canela, M. Glycolysis/gluconeogenesis- and tricarboxylic acid cycle-related metabolites, Mediterranean diet, and type 2 diabetes. Am J Clin Nutr. 2020. 111:835-844. doi:10.1093/ajcn/nqaa016 | Size of Study Groups
195 | Gunther, J, Hoffmann, J, Stecher, L, Spies, M, Geyer, K, Raab, R, Meyer, D, Rauh, K, Hauner, H. Associations between antenatal lifestyle and the risk for gestational diabetes mellitus in the GeliS trial-an exploratory secondary cohort analysis. Obesity facts. 2021. 14:102-. doi:10.1159/000515911 | Publication Status
196 | Guo, X, Liu, S, Zeng, X, Su, L, Huang, D, Ma, X, Liu, B, Tang, P, Qiu, X. Dietary patterns and diabetes risk in Southern Chinese in Guangxi Zhuang autonomous region. International Journal of Diabetes in Developing Countries. 2023. 43:258. | Study Design
197 | Gürdeniz G, Uusitupa M, Hermansen K, Savolainen MJ, Schwab U, Kolehmainen M, Brader L, Cloetens L, Herzig KH, Hukkanen J, Rosqvist F, Ulven SM, Gunnarsdóttir I, Thorsdottir I, Oresic M, Poutanen KS, Risérus U, Åkesson B, Dragsted LO. Analysis of the SYSDIET Healthy Nordic Diet randomized trial based on metabolic profiling reveal beneficial effects on glucose metabolism and blood lipids. 41. | Intervention/Exposure; Outcome
198 | Ha, K, Joung, H, Song, Y. Inadequate fat or carbohydrate intake was associated with an increased incidence of type 2 diabetes mellitus in Korean adults: A 12-year community-based prospective cohort study. Diabetes Research and Clinical Practice. 2019. 148:254-261. doi:10.1016/j.diabres.2019.01.024 | Intervention/Exposure
199 | Hailili, Gulisiya, Chen, Zhen, Tian, Tian, Fu, Wen-Hui, Pei, Hua-Lian, Mahan, Yeledan, Luo, Tao, Alimu, Dilibaier, Wang, Lu, Zhang, Guo-Zhen, Liu, Li-Rong, Wang, Duo-Lao, Dai, Jiang-Hong. Dietary patterns and their associations with the metabolic syndrome and predicted 10-year risk of CVD in northwest Chinese adults. British Journal of Nutrition. 2021. 126:913-922. doi:10.1017/S000711452000478X | Outcome
200 | Hall, M, Walicka, M, Panczyk, M, Traczyk, I. Assessing Long-Term Impact of Dietary Interventions on Occurrence of Symptoms Consistent with Hypoglycemia in Patients without Diabetes: A One-Year Follow-Up Study. Nutrients. 2022. 14. | Outcome
201 | Han, L, Zhang, T, You, D, Chen, W, Bray, G, Sacks, F, Qi, L. Temporal and mediation relations of weight loss, and changes in insulin resistance and blood pressure in response to 2-year weight-loss diet interventions: the POUNDS Lost trial. European Journal of Nutrition. 2022. 61:269. | Intervention/Exposure
202 | Hao Y, Qu L, Guo Y, Ma L, Guo M, Zhu Y, Jin Y, Gu Q, Zhang Y, Sun W. Association of pre-pregnancy low-carbohydrate diet with maternal oral glucose tolerance test levels in gestational diabetes. 22. | Study Design; Intervention/Exposure
203 | Hardy DS, Racette SB, Garvin JT, Gebrekristos HT, Mersha TB. Ancestry specific associations of a genetic risk score, dietary patterns and metabolic syndrome: a longitudinal ARIC study. 14. | Outcome
204 | Harper, CA, Smythe, K, Wong, VW, Rollo, ME, Collins, CE. Comparison of pre-diagnosis dietary intake of women with gestational diabetes mellitus to dietary recommendations. Midwifery. 2021. 100:103032. doi:10.1016/j.midw.2021.103032 | Study Design
205 | Harreiter, J, Simmons, D, Desoye, G, Corcoy, R, Adelantado, JM, Devlieger, R, Galjaard, S, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LLT, Dunne, F, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Mantaj, U, Hill, D, Jelsma, JGM, Snoek, FJ, Leutner, M, Lackinger, C, Worda, C, Bancher-Todesca, D, Scharnagl, H, Van Poppel, MNM, Kautzky-Willer, A. Nutritional lifestyle intervention in obese pregnant women, including lower carbohydrate intake, is associated with increased maternal free fatty acids, 3-b-hydroxybutyrate, and fasting glucose concentrations: A secondary factorial analysis of the European multicenter, randomized controlled DALI lifestyle intervention trial. Diabetes Care. 2019. 42:1380-1389. doi:10.2337/dc19-0418 | Intervention/Exposure
206 | Hasbullah, F, Mohd Yusof, B, Appannah, G, Abdul Ghani, R, Mat Daud, Z, Chee, W, Abas, F. Dietary Patterns and Type 2 Diabetes Risk in Malaysian Women With and Without History of Gestational Diabetes Mellitus. Journal of the Academy of Nutrition & Dietetics. 2021. 121:A22-A22. doi:10.1016/j.jand.2021.06.047 | Publication Status
207 | Haywood, CJ, Prendergast, LA, Lim, R, Lappas, M, Lim, WK, Proietto, J. Obesity in older adults: Effect of degree of weight loss on cardiovascular markers and medications. Clinical Obesity. 2019. 9. doi:10.1111/cob.12316 | Intervention/Exposure
208 | He M, Wang J, Liang Q, Li M, Guo H, Wang Y, Deji C, Sui J, Wang YW, Liu Y, Zheng Y, Qian B, Chen H, Ma M, Su S, Geng H, Zhou WX, Guo X, Zhu WZ, Zhang M, Chen Z, Rensen PCN, Hui CC, Wang Y, Shi B. Time-restricted eating with or without low-carbohydrate diet reduces visceral fat and improves metabolic syndrome: A randomized trial. | Intervention/Exposure
209 | He Y, Fang Y, Bromage S, Fung TT, Bhupathiraju SN, Batis C, Deitchler M, Fawzi W, Stampfer MJ, Hu FB, Willett WC, Li Y. Application of the Global Diet Quality Score in Chinese Adults to Evaluate the Double Burden of Nutrient Inadequacy and Metabolic Syndrome. 151. | Study Design
210 | He YM, Chen WL, Kao TW, Wu LW, Yang HF, Peng TC. Relationship between Ideal Cardiovascular Health and Incident Proteinuria: A 5 Year Retrospective Cohort Study. 14. | Outcome; Country
211 | He, D, Qiao, Y, Xiong, S, Liu, S, Ke, C, Shen, Y. Association between Dietary Quality and Prediabetes based on the Diet Balance Index. Sci Rep. 2020. 10:3190. doi:10.1038/s41598-020-60153-9 | Study Design; Country
212 | Hendryx, M, Dinh, P, Chow, A, Kroenke, CH, Hingle, M, Shadyab, AH, Garcia, L, Howard, BV, Luo, J. Lifestyle and Psychosocial Patterns and Diabetes Incidence Among Women with and Without Obesity: a Prospective Latent Class Analysis. Prev Sci. 2020. 21:850-860. doi:10.1007/s11121-02001130-6 | Intervention/Exposure; Confounders
213 | Henning, SM, Yang, J, Woo, SL, Lee, RP, Huang, J, Rasmusen, A, Carpenter, CL, Thames, G, Gilbuena, I, Tseng, CH, etal, . Hass Avocado Inclusion in a Weight-Loss Diet Supported Weight Loss and Altered Gut Microbiota: a 12-Week Randomized, Parallel-Controlled Trial. Current developments in nutrition. 2019. 3. doi:10.1093/cdn/nzz068 | Intervention/Exposure; Publication Status
214 | Hermenegildo-López Y, Donat-Vargas C, Sandoval-Insausti H, Moreno-Franco B, Rodríguez-Ayala M, Rey-García J, Banegas JR, Rodríguez-Artalejo F, Guallar-Castillón P. A Higher Intake of Energy at Dinner Is Associated with Incident Metabolic Syndrome: A Prospective Cohort Study in Older Adults. 13. | Intervention/Exposure
215 | Hernández-Alonso, P, Giardina, S, Cañueto, D, Salas-Salvadó, J, Cañellas, N, Bulló, M. Changes in Plasma Metabolite Concentrations after a Low-Glycemic Index Diet Intervention. Molecular nutrition & food research. 2019. 63:e1700975. doi:10.1002/mnfr.201700975 | Intervention/Exposure
216 | Hernando-Redondo J, Toloba A, Benaiges D, Salas-Salvadó J, Martínez-Gonzalez MA, Corella D, Estruch R, Tinahones FJ, Ros E, Goday A, Castañer O, Fitó M. Mid- and long-term changes in satiety-related hormones, lipid and glucose metabolism, and inflammation after a Mediterranean diet intervention with the goal of losing weight: A randomized, clinical trial. 9. | Intervention/Exposure; Comparator
217 | Hinkle, SN, Bao, W, Wu, J, Sun, Y, Ley, SH, Tobias, DK, Qian, F, Rawal, S, Zhu, Y, Chavarro, JE, Hu, FB, Zhang, C. Association of Habitual Alcohol Consumption with Long-term Risk of Type 2 Diabetes among Women with a History of Gestational Diabetes. JAMA Network Open. 2021. 4. | Intervention/Exposure
218 | Hjorth, MF, Astrup, A, Zohar, Y, Urban, LE, Sayer, RD, Patterson, BW, Herring, SJ, Klein, S, Zemel, BS, Foster, GD, Wyatt, HR, Hill, JO. Personalized nutrition: pretreatment glucose metabolism determines individual long-term weight loss responsiveness in individuals with obesity on low-carbohydrate versus low-fat diet. International Journal of Obesity. 2019. 43:2037-2044. doi:10.1038/s41366-018-0298-4 | Intervention/Exposure
219 | Hjorth, MF, Bray, GA, Zohar, Y, Urban, L, Miketinas, DC, Williamson, DA, Ryan, DH, Rood, J, Champagne, CM, Sacks, FM, Astrup, A. Pretreatment fasting glucose and insulin as determinants of weight loss on diets varying in macronutrients and dietary fibers—The POUNDS LOST study. Nutrients. 2019. 11. doi:10.3390/nu11030586 | Intervention/Exposure
220 | Hjorth, MF, Corella, D, Astrup, A, Ruiz-Canela, M, Salas-Salvado, J, Fito, M, Martínez-González, J, Romaguera, D, Lapetra, J, Estruch, R, Serra-Majem, L, Pinto, X, Alonso-Gómez, Á, Martínez, JA, Martínez-González, MA. High fat diets for weight loss among subjects with elevated fasting glucose levels: The PREDIMED study. Obesity Medicine. 2020. 18. doi:10.1016/j.obmed.2020.100210 | Intervention/Exposure; Outcome; Comparator
221 | Holder, M, Kapellen, T, Ziegler, R, Bürger-Büsing, J, Danne, T, Dost, A, Holl, RW, Holterhus, P-M, Karges, B, Kordonouri, O, Lange, K, Müller, S, Raile, K, Schweizer, R, Von Sengbusch, S, Stachow, R, Wagner, V, Wiegand, S, Neu, A. Diagnosis, Therapy and Follow-Up of Diabetes Mellitus in Children and Adolescents. Experimental and Clinical Endocrinology and Diabetes. 2022. 130:S49. | Study Design; Publication Status
222 | Hosseini-Esfahani F, Beheshti N, Koochakpoor G, Mirmiran P, Azizi F. Meat Food Group Intakes and the Risk of Type 2 Diabetes Incidence. 9. | Intervention/Exposure
223 | Hosseinpour-Niazi S, Mirmiran P, Hadaegh F, Mahdavi M, Khalili D, Daneshpour MS, Momenan AA, Azizi F. Improvement of glycemic indices by a hypocaloric legume-based DASH diet in adults with type 2 diabetes: a randomized controlled trial. | Health Status
224 | Hrolfsdottir, L, Gunnarsdottir, I, Birgisdottir, BE, Hreidarsdottir, IT, Smarason, AK, Hardardottir, H, Halldorsson, TI. Can a simple dietary screening in early pregnancy identify dietary habits associated with gestational diabetes?. Nutrients. 2019. 11. doi:10.3390/nu11081868 | Data Overlap
225 | Hu, C, Mu, Y, Wan, Q, Qin, Y, Hu, R, Shi, L, Su, Q, Yu, X, Yan, L, Qin, G, Tang, X, Chen, G, Gao, Z, Wang, G, Shen, F, Luo, Z, Chen, L, Huo, Y, Li, Q, Ye, Z, Zhang, Y, Liu, C, Wang, Y, Wu, S, Yang, T, Deng, H, Chen, L, Zhao, J, Lu, J, Lin, L, Li, M, Du, R, Xu, M, Xu, Y, Wang, T, Zhao, Z, Chen, Y, Li, D, Bi, Y, Wang, W, Ning, G, Reaction Study Group. Association between birth weight and diabetes: Role of body mass index and lifestyle in later life. J Diabetes. 2020. 12:10-20. doi:10.1111/17530407.12960 | Intervention/Exposure
226 | Hu, J, Oken, E, Aris, IM, Lin, PID, Ma, Y, Ding, N, Gao, M, Wei, X, Wen, D. Dietary patterns during pregnancy are associated with the risk of gestational diabetes mellitus: Evidence from a chinese prospective birth cohort study. Nutrients. 2019. 11. doi:10.3390/nu11020405 | Data Overlap
227 | Hua Y, Zhang Z, Liu A. Long-Term Diet Quality and Risk of Diabetes in a National Survey of Chinese Adults. 14. | Outcome
228 | Huang, L, Shang, L, Yang, W, Li, D, Qi, C, Xin, J, Wang, S, Yang, L, Zeng, L, Chung, MC. High starchy food intake may increase the risk of adverse pregnancy outcomes: a nested case-control study in the Shaanxi province of Northwestern China. BMC Pregnancy Childbirth. 2019. 19:362. doi:10.1186/s12884-019-2524-z | Outcome
229 | Huo Y, Cao S, Liu J, Zhang B, Xu K, Wang Y, Liu H, Yang P, Zeng L, Yan H, Dang S, Mi B. The Association between Plant-Based Diet Indices and Metabolic Syndrome in Chinese Adults: Longitudinal Analyses from the China Health and Nutrition Survey. 15. | Outcome
230 | Iglesies-Grau, J, Dionne, V, Bherer, L, Bouabdallaoui, N, Aubut, L, Besnier, F, Bertholet, J, Berthiaume, A, Bisaillon, M, Gayda, M, Gagnon, C, Hamrioui, N, Latour, É, L’Allier, PL, Marie-Hélène, MC, Nigam, A, Pelletier, V, Tessier, G, Juneau, M. Metabolic Improvements and Remission of Prediabetes and Type 2 Diabetes: Results From a Multidomain Lifestyle Intervention Clinic. Canadian Journal of Diabetes. 2023. 47:185. | Intervention/Exposure
231 | Irct20180201038585N, . The effect of DASH diet in subjects with metabolic syndrome. https://trialsearch.who.int/Trial2.aspx?TrialID=IRCT20180201038585N12. 2022. | Publication Status
232 | Irct20211106052979N, . The effect of aerobic training and DASH diet on insulin resistance and sex hormones in women with polycystic ovary syndrome. https://trialsearch.who.int/Trial2.aspx?TrialID=IRCT20211106052979N1. 2021. | Study Duration; Publication Status
233 | Ismael, S, Silvestre, MP, Vasques, M, Araújo, JR, Morais, J, Duarte, MI, Pestana, D, Faria, A, Pereira-Leal, J, Vaz, J, Ribeiro, P, Teixeira, D, Marques, C, Calhau, C. Gut microbial richness as an earlier biomarker of Mediterranean diet intervention in type 2 diabetes metabolic control. Proceedings of the Nutrition Society. 2021. 80:1-1. doi:10.1017/S002966512100080X | Publication Status
234 | Ismael, S, Silvestre, MP, Vasques, M, Araujo, JR, Morais, J, Duarte, MI, Pestana, D, Faria, A, Pereira-Leal, JB, Vaz, J, Ribeiro, P, Teixeira, D, Marques, C, Calhau, C. A Pilot Study on the Metabolic Impact of Mediterranean Diet in Type 2 Diabetes: Is Gut Microbiota the Key?. Nutrients. 2021. 13. doi:10.3390/nu13041228 | Study Design; Health Status
235 | Issa, BG, Harvie, M, McDiarmid, S, Johnson, R, Vyas, A, Aglan, A, Ruane, H, Hulme, A, Sellers, K, Jones, LA, etal, . Manchester Intermittent versus Daily diet Diabetes App Study (MIDDAS). Pilot RCT comparing a continuous with an intermittent low energy diet in patients with type 2 diabetes. Diabetologia. 2020. 63:S104-S105. doi:10.1007/s00125-020-05221-5 | Health Status; Study Duration
236 | Ivan CR, Messina A, Cibelli G, Messina G, Polito R, Losavio F, Torre E, Monda V, Monda M, Quiete S, Casula E, Napoli N, Defeudis G. Italian Ketogenic Mediterranean Diet in Overweight and Obese Patients with Prediabetes or Type 2 Diabetes. 14. | Study Duration
237 | Izaola, O, Primo, D, De Luis, D. Dietary Intervention during 9 Months with a Hypocaloric Diet, Interaction of the Genetic Variant of Adiponectin Gene rs822393 with Metabolic Parameters. Disease Markers. 2022. 2022. | Study Design; Intervention/Exposure
238 | Jannasch, F, Kröger, J, Agnoli, C, Barricarte, A, Boeing, H, Cayssials, V, Colorado-Yohar, S, Dahm, CC, Dow, C, Fagherazzi, G, Franks, PW, Freisling, H, Gunter, MJ, Kerrison, ND, Key, TJ, Khaw, KT, Kühn, T, Kyro, C, Mancini, FR, Mokoroa, O, Nilsson, P, Overvad, K, Palli, D, Panico, S, García, JRQ, Rolandsson, O, Sacerdote, C, Sánchez, MJ, Sahrai, MS, Schübel, R, Sluijs, I, Spijkerman, AMW, Tjonneland, A, Tong, TYN, Tumino, R, Riboli, E, Langenberg, C, Sharp, SJ, Forouhi, NG, Schulze, MB, Wareham, NJ. Generalizability of a Diabetes-Associated Country-Specific Exploratory Dietary Pattern Is Feasible across European Populations. Journal of Nutrition. 2019. 149:1047-1055. doi:10.1093/jn/nxz031 | Study Design
239 | Jenkins, DavidJA, Srichaikul, Korbua, Kendall, CyrilWC, Sievenpiper, JohnL. Bean, fruit, and vegetable fiber, but not cereal fiber are associated with reduced mortality in Japan. American Journal of Clinical Nutrition. 2020. 111:941-943. doi:10.1093/ajcn/nqaa045 | Publication Status
240 | Jeziorek M, Szuba A, Kujawa K, Regulska-Ilow B. The Effect of a Low-Carbohydrate, High-Fat Diet versus Moderate-Carbohydrate and Fat Diet on Body Composition in Patients with Lipedema. 15. | Intervention/Exposure; Outcome
241 | Jia Y, Guo D, Sun L, Shi M, Zhang K, Yang P, Zang Y, Wang Y, Liu F, Chen GC, Zhang Y, Zhu Z. Diet, Lifestyle Behaviour and Other Risk Factors Associated With Type 2 Diabetes Beyond Body Mass Index: A Mendelian Randomization Study. | Intervention/Exposure
242 | Jin, SM, Ahn, J, Park, J, Hur, KY, Kim, JH, Lee, MK. East Asian Diet-Mimicking Diet Plan Based on the Mediterranean Diet and the DASH Diet in Adults with Type 2 Diabetes: a Randomized Controlled Trial. Journal of diabetes investigation. 2020. doi:10.1111/jdi.13384 | Health Status
243 | Johansson, A, Acosta, S, Mutie, PM, Sonestedt, E, Engström, G, Drake, I. Components of a healthy diet and different types of physical activity and risk of atherothrombotic ischemic stroke: A prospective cohort study. Frontiers in Cardiovascular Medicine. 2022. 9. | Outcome
244 | Jospe, MichelleR, Roy, Melyssa, Brown, RachelC, Haszard, JillianJ, Meredith-Jones, Kim, Fangupo, LouiseJ, Osborne, Hamish, Fleming, ElizabethA, Taylor, RachaelW. Intermittent fasting, Paleolithic, or Mediterranean diets in the real world: exploratory secondary analyses of a weight-loss trial that included choice of diet and exercise. American Journal of Clinical Nutrition. 2020. 111:503-514. doi:10.1093/ajcn/nqz330 | Size of Study Groups
245 | JP Goode, KJ Smith, M Breslin, M Kilpatrick, T Dwyer, AJ Venn, CG Magnussen. A healthful plant-based eating pattern is longitudinally associated with higher insulin sensitivity in Australian adults. The Journal of nutrition. 2023. | Size of Study Groups
246 | Juna, CF, Cho, Y, Ham, D, Joung, H. Association of carbohydrate and fat intake with prevalence of metabolic syndrome can be modified by physical activity and physical environment in ecuadorian adults: The ensanut-ecu study. Nutrients. 2021. 13. | Study Design
247 | Kafyra M, Kalafati IP, Katsareli EA, Lambrinou S, Varlamis I, Kaliora AC, Dedoussis GV. The iMPROVE Study; Design, Dietary Patterns, and Development of a Lifestyle Index in Overweight and Obese Greek Adults. 13. | Study Design; Outcome
248 | Kahleova H, Berrien-Lopez R, Holtz D, Green A, Sheinberg R, Gujral H, Holubkov R, Barnard ND. Nutrition for Hospital Workers During a Crisis: Effect of a Plant-Based Dietary Intervention on Cardiometabolic Outcomes and Quality of Life in Healthcare Employees During the COVID-19 Pandemic. 16. | Intervention/Exposure
249 | Kahleova H, McCann J, Alwarith J, Rembert E, Tura A, Holubkov R, Barnard ND. A plant-based diet in overweight adults in a 16-week randomized clinical trial: The role of dietary acid load. 44. | Intervention/Exposure; Outcome
250 | Kahleova H, Rembert E, Nowak A, Holubkov R, Barnard ND. Effect of a diet intervention on cardiometabolic outcomes: Does race matter? A randomized clinical trial. 41. | Intervention/Exposure; Publication Status
251 | Kahleova, H, Hlozkova, A, Fleeman, R, Fletcher, K, Holubkov, R, Barnard, ND. Fat quantity and quality, as part of a low-fat, vegan diet, are associated with changes in body composition, insulin resistance, and insulin secretion. A 16-week randomized controlled trial. Nutrients. 2019. 11. doi:10.3390/nu11030615 | Intervention/Exposure; Comparator
252 | Kahleova, H, Petersen, KF, Shulman, GI, Alwarith, J, Rembert, E, Tura, A, Hill, M, Holubkov, R, Barnard, ND. A dietary intervention to alter insulin sensitivity, intramyocellular and hepatocellular lipids, postprandial metabolism, and body weight: a 16-week randomised trial. Diabetologia. 2020. 63:S16-S17. doi:10.1007/s00125-020-05221-5 | Publication Status
253 | Kahleova, H, Petersen, KF, Shulman, GI, Alwarith, J, Rembert, E, Tura, A, Hill, M, Holubkov, R, Barnard, ND. Effect of a Low-Fat Vegan Diet on Body Weight, Insulin Sensitivity, Postprandial Metabolism, and Intramyocellular and Hepatocellular Lipid Levels in Overweight Adults: A Randomized Clinical Trial. JAMA Netw Open. 2020. 3:e2025454. doi:10.1001/jamanetworkopen.2020.25454 | Intervention/Exposure; Comparator
254 | Kahleova, H, Rembert, E, Alwarith, J, Yonas, WN, Tura, A, Holubkov, R, Agnello, M, Chutkan, R, Barnard, ND. Effects of a Low-Fat Vegan Diet on Gut Microbiota in Overweight Individuals and Relationships with Body Weight, Body Composition, and Insulin Sensitivity. A Randomized Clinical Trial. Nutrients. 2020. 12. doi:10.3390/nu12102917 | Intervention/Exposure
255 | Kalam, F, Gabel, K, Cienfuegos, S, Wiseman, E, Ezpeleta, M, Pavlou, V, Varady, KA. Changes in subjective measures of appetite during 6 months of alternate day fasting with a low carbohydrate diet. Clinical Nutrition ESPEN. 2021. 41:417-422. doi:10.1016/j.clnesp.2020.10.007 | Intervention/Exposure
256 | Kalam, F, Gabel, K, Cienfuegos, S, Wiseman, E, Ezpeleta, M, Steward, M, Pavlou, V, Varady, KA. Alternate day fasting combined with a low-carbohydrate diet for weight loss, weight maintenance, and metabolic disease risk reduction. Obesity Science and Practice. 2019. 5:531-539. doi:10.1002/osp4.367 | Intervention/Exposure
257 | Kalkuz, S, Demircan, A. Effects of the Mediterranean diet adherence on body composition, blood parameters and quality of life in adults. Postgrad Med J. 2020. doi:10.1136/postgradmedj-2020-138667 | Study Design
258 | Kauffman, SAE, Averill, MM, Delaney, JAC, Lemaitre, RN, Howard, BV, Fretts, AM. Associations of diet quality and blood serum lipoprotein levels in a population at high risk for diabetes: the Strong Heart Family Study. Eur J Clin Nutr. 2020. 74:1084-1090. doi:10.1038/s41430-019-0539-1 | Outcome
259 | Kawada, Tomoyuki. Egg consumption and incident type 2 diabetes: A risk assessment. Clinical Nutrition. 2021. 40:5417-5417. doi:10.1016/j.clnu.2021.09.026 | Publication Status
260 | Kawada, Tomoyuki. Red meat consumption and biological markers of metabolic disorders. 2021. 60:2999-3000. doi:10.1007/s00394-021-02609-w | Publication Status
261 | Keenan S, Cooke MB, Chen WS, Wu S, Belski R. The Effects of Intermittent Fasting and Continuous Energy Restriction with Exercise on Cardiometabolic Biomarkers, Dietary Compliance, and Perceived Hunger and Mood: Secondary Outcomes of a Randomised, Controlled Trial. 14. | Intervention/Exposure; Outcome
262 | Kenđel Jovanović, G, Mrakovcic-Sutic, I, Pavičić Žeželj, S, Benjak Horvat, I, Šuša, L, Rahelić, D, Klobučar Majanović, S. Metabolic and Hepatic Effects of Energy-Reduced Anti-Inflammatory Diet in Younger Adults with Obesity. Canadian Journal of Gastroenterology and Hepatology. 2021. 2021. doi:10.1155/2021/6649142 | Intervention/Exposure
263 | Kendel Jovanovic, G, Mrakovcic-Sutic, I, Pavicic Zezelj, S, Susa, B, Rahelic, D, Klobucar Majanovic, S. The Efficacy of an Energy-Restricted Anti-Inflammatory Diet for the Management of Obesity in Younger Adults. Nutrients. 2020. 12. doi:10.3390/nu12113583 | Intervention/Exposure
264 | Kerr JA, Liu RS, Gasser CE, Mensah FK, Burgner D, Lycett K, Gillespie AN, Juonala M, Clifford SA, Olds T, Saffery R, Gold L, Liu M, Azzopardi P, Edwards B, Dwyer T, Wake M. Diet quality trajectories and cardiovascular phenotypes/metabolic syndrome risk by 11-12 years. 45. | Intervention/Exposure; Outcome
265 | Kesary, Y, Avital, K, Hiersch, L. Maternal plant-based diet during gestation and pregnancy outcomes. Arch Gynecol Obstet. 2020. 302:887-898. doi:10.1007/s00404-020-05689-x | Study Design
266 | Kesse-Guyot, E, Rebouillat, P, Payrastre, L, Alles, B, Fezeu, LK, Druesne-Pecollo, N, Srour, B, Bao, W, Touvier, M, Galan, P, Hercberg, S, Lairon, D, Baudry, J. Prospective association between organic food consumption and the risk of type 2 diabetes: findings from the NutriNet-Sante cohort study. Int J Behav Nutr Phys Act. 2020. 17:136. doi:10.1186/s12966-020-01038-y | Intervention/Exposure
267 | Khan, I, Kwon, M, Shivappa, N, Hebert J R, Kim, MK. Proinflammatory Dietary Intake is Associated with Increased Risk of Metabolic Syndrome and Its Components: Results from the Population-Based Prospective Study. Nutrients. 2020. 12. doi:10.3390/nu12041196 | Intervention/Exposure
268 | Kharmats AY, Popp C, Hu L, Berube L, Curran M, Wang C, Pompeii ML, Li H, Bergman M, St-Jules DE, Segal E, Schoenthaler A, Williams N, Schmidt AM, Barua S, Sevick MA. A randomized clinical trial comparing low-fat versus precision nutrition-based diets for weight loss: impact on glycemic variability and HbA1c. | Intervention/Exposure
269 | Khoury N, Gómez-Donoso C, Martínez MÁ, Martínez-González MÁ, Corella D, Fitó M, Martínez JA, Alonso-Gómez ÁM, Wärnberg J, Vioque J, Romaguera D, León-Acuña A, Tinahones FJ, Santos-Lozano JM, Serra-Majem L, Massó Guijarro P, Tur JA, Martín Sánchez V, Pintó X, Delgado-Rodríguez M, Matía-Martín P, Vidal J, Vázquez C, Daimiel L, Ros E, Bes-Rastrollo M, Barragan R, Castañer O, Torres-Peña JD, Notario-Barandiaran L, Muñoz-Bravo C, Abete I, Prohens L, Cano-Ibáñez N, Tojal Sierra L, Fernández-García JC, Sayon-Orea C, Pascual M, Sorli JV, Zomeño D, Peña-Orihuela PJ, Signes-Pastor AJ, Basterra-Gortari FJ, Schröeder H, Salas Salvadó J, Babio N. Associations Between the Modified Food Standard Agency Nutrient Profiling System Dietary Index and Cardiovascular Risk Factors in an Elderly Population. 9. | Outcome
270 | Killeen SL, Phillips CM, Delahunt A, Yelverton CA, Shivappa N, Hébert JR, Kennelly MA, Cronin M, Mehegan J, McAuliffe FM. Effect of an Antenatal Lifestyle Intervention on Dietary Inflammatory Index and Its Associations with Maternal and Fetal Outcomes: A Secondary Analysis of the PEARS Trial. 13. | Intervention/Exposure
271 | Kim J, Kim M, Shin Y, Cho JH, Lee D, Kim Y. Association between Dietary Diversity Score and Metabolic Syndrome in Korean Adults: A Community-Based Prospective Cohort Study. 14. | Other:; KoGES; Intervention/Exposure
272 | Kim MJ, Hur HJ, Jang DJ, Kim MS, Park S, Yang HJ. Inverse association of a traditional Korean diet composed of a multigrain rice-containing meal with fruits and nuts with metabolic syndrome risk: The KoGES. 9. | Study Design
273 | Kim Y, Kim YM, Shin MH, Koh SB, Chang Kim H, Kim MK. Empirically identified dietary patterns and metabolic syndrome risk in a prospective cohort study: The Cardiovascular Disease Association Study. 41. | Outcome
274 | Kim, H, Lee, K, Rebholz, CM, Kim, J. Association between unhealthy plant-based diets and the metabolic syndrome in adult men and women: a population-based study in South Korea. Br J Nutr. 2021. 125:577-590. doi:10.1017/S0007114520002895 | Study Design
275 | Kim, H, Lee, K, Rebholz, CM, Kim, J. Plant-based diets and incident metabolic syndrome: Results from a South Korean prospective cohort study. PLoS Med. 2020. 17:e1003371. doi:10.1371/journal.pmed.1003371 | Outcome
276 | Kim, HS, Lee, H, Provido, SMP, Kang, M, Chung, GH, Hong, S, Yu, SH, Lee, CB, Lee, JE. Association Between Diet Quality and Prevalence of Obesity, Dyslipidemia, and Insulin Resistance Among Filipino Immigrant Women in Korea: The Filipino Women’s Diet and Health Study. Front Public Health. 2021. 9:647661. doi:10.3389/fpubh.2021.647661 | Study Design
277 | Kim, MJ, Lim, H-S, Lee, H-H, Kim, T-H, Park, Y. Dietary assessment, nutrition knowledge, and pregnancy outcome in high-risk pregnant Korean women. Clinical and Experimental Obstetrics and Gynecology. 2021. 48:1178. | Intervention/Exposure; Comparator
278 | Kim, MJ, Park, S, Yang, HJ, Shin, P-K, Hur, HJ, Park, S-J, Lee, K-H, Hong, M, Kim, JH, Choi, S-W, Lee, H-J, Kim, M-S. Alleviation of Dyslipidemia via a Traditional Balanced Korean Diet Represented by a Low Glycemic and Low Cholesterol Diet in Obese Women in a Randomized Controlled Trial. Nutrients. 2022. 14. | Study Duration
279 | Kim, SH, Kim, HJ, Shin, G. Self-Management Mobile Virtual Reality Program for Women with Gestational Diabetes. Int J Environ Res Public Health. 2021. 18. doi:10.3390/ijerph18041539 | Intervention/Exposure
280 | Kinnunen, Tarja, Liu, Yangbo, Koivisto, Anna-Maija, Virtanen, Suvi, Luoto, Riitta. Effects of dietary counselling on micronutrient intakes in pregnant women in Finland. Maternal & Child Nutrition. 2021. 17:1-10. doi:10.1111/mcn.13203 | Intervention/Exposure
281 | Koeder C, Kranz RM, Anand C, Husain S, Alzughayyar D, Schoch N, Hahn A, Englert H. Effect of a 1-year controlled lifestyle intervention on body weight and other risk markers (the Healthy Lifestyle Community Programme, cohort 2). | Intervention/Exposure; Comparator
282 | Kohl, J, Brame, J, Hauff, P, Wurst, R, Sehlbrede, M, Fichtner, UA, Armbruster, C, Tinsel, I, Maiwald, P, Farin-Glattacker, E, Fuchs, R, Gollhofer, A, K?nig, D. Effects of a Web-Based Weight Loss Program on the Healthy Eating Index-NVS in Adults with Overweight or Obesity and the Association with Dietary, Anthropometric and Cardiometabolic Variables: A Randomized Controlled Clinical Trial. Nutrients. 2023. 15. | Size of Study Groups
283 | Koloverou, E, Panagiotakos, DB, Georgousopoulou, EN, Grekas, A, Christou, A, Chatzigeorgiou, M, Chrysohoou, C, Tousoulis, D, Stefanadis, C, Pitsavos, C, Skoumas, Y, Katinioti, N, Papadimitriou, L, Masoura, C, Vellas, S, Lentzas, Y, Kambaxis, M, Palliou, K, Metaxa, V, Ntzouvani, A, Mpougatsas, D, Skourlis, N, Papanikolaou, C, Kouli, G-M, Christou, A, Zana, A, Ntertimani, M, Kalogeropoulou, A, Pitaraki, E, Laskaris, A, Hatzigeorgiou, M, Grekas, A, Vassiliadou, C, Dedoussis, G, Toutouza-Giotsa, M, Tselika, C, Poulopoulou, S. Dietary patterns and 10-year (2002-2012) incidence of type 2 diabetes: Results from the ATTICA cohort study. Review of Diabetic Studies. 2016. 13:246. | Publication Date
284 | Korat, Ardisson AndresV, Li, Yanping, Sacks, Frank, Rosner, Bernard, Willett, WalterC, Hu, FrankB, Sun, Qi. Dairy fat intake and risk of type 2 diabetes in 3 cohorts of US men and women. American Journal of Clinical Nutrition. 2019. 110:1192-1200. doi:10.1093/ajcn/nqz176 | Intervention/Exposure
285 | Kouvari M, Tsiampalis T, Kosti RI, Naumovski N, Chrysohoou C, Skoumas J, Pitsavos CS, Panagiotakos DB, Mantzoros CS. Quality of plant-based diets is associated with liver steatosis, which predicts type 2 diabetes incidence ten years later: Results from the ATTICA prospective epidemiological study. 41. | Study Design; Outcome
286 | Kouvari, M, Boutari, C, Chrysohoou, C, Fragkopoulou, E, Antonopoulou, S, Tousoulis, D, Pitsavos, C, Panagiotakos, DB, Mantzoros, CS, Attica study Investigators. Mediterranean diet is inversely associated with steatosis and fibrosis and decreases ten-year diabetes and cardiovascular risk in NAFLD subjects: Results from the ATTICA prospective cohort study. Clin Nutr. 2021. 40:3314-3324. doi:10.1016/j.clnu.2020.10.058 | Intervention/Exposure; Outcome; Comparator
287 | Kouvari, M, Panagiotakos, DB, Yannakoulia, M, Georgousopoulou, E, Critselis, E, Chrysohoou, C, Tousoulis, D, Pitsavos, C. Transition from metabolically benign to metabolically unhealthy obesity and 10-year cardiovascular disease incidence: The ATTICA cohort study. Metabolism: Clinical and Experimental. 2019. 93:18-24. doi:10.1016/j.metabol.2019.01.003 | Intervention/Exposure; Outcome
288 | Koyuncu, Z, Kadak, MT, Tarakçıoğlu, MC, Bingöl Çağlayan, RH, Doğangün, B, Ercan, O. Eatıng behavıours and alexıthymıc features of obese and overweıght adolescents. Pediatrics international : official journal of the Japan Pediatric Society. 2021. | Intervention/Exposure
289 | Kunath, J, Günther, J, Rauh, K, Hoffmann, J, Stecher, L, Rosenfeld, E, Kick, L, Ulm, K, Hauner, H. Effects of a lifestyle intervention during pregnancy to prevent excessive gestational weight gain in routine care - the cluster-randomised GeliS trial. BMC Medicine. 2019. 17. doi:10.1186/s12916-018-1235-z | Intervention/Exposure
290 | Kunduraci, YE, Ozbek, H. Does the Energy Restriction Intermittent Fasting Diet Alleviate Metabolic Syndrome Biomarkers? A Randomized Controlled Trial. Nutrients. 2020. 12. doi:10.3390/nu12103213 | Intervention/Exposure
291 | Kwon, Y-J, Park, K, Lee, J-H. Low-protein diet is inversely related to the incidence of chronic kidney disease in middle-aged and older adults: results from a community-based prospective cohort study. European journal of nutrition. 2022. | Intervention/Exposure; Outcome
292 | Lafrenière, J, Carbonneau, E, Laramée, C, Corneau, C, Robitaille, J, Labonté, ME, Lamarche, B, Lemieux, S. Is the Canadian healthy eating index 2007 an appropriate diet indicator of metabolic health? insights from dietary pattern analysis in the PREDISE study. Nutrients. 2019. 11. doi:10.3390/nu11071597 | Study Design
293 | Lagstrom, H, Stenholm, S, Akbaraly, T, Pentti, J, Vahtera, J, Kivimaki, M, Head, J. Diet quality as a predictor of cardiometabolic disease-free life expectancy: the Whitehall II cohort study. Am J Clin Nutr. 2020. 111:787-794. doi:10.1093/ajcn/nqz329 | Outcome
294 | Lai JS, Colega MT, Godfrey KM, Tan KH, Yap F, Chong YS, Lee YS, Eriksson JG, Chan SY, Chong MFF. Changes in Diet Quality from Pregnancy to 6 Years Postpregnancy and Associations with Cardiometabolic Risk Markers. 15. | Size of Study Groups
295 | Lai KZH, Semnani-Azad Z, Retnakaran R, Harris SB, Hanley AJ. Changes in adiposity mediate the associations of diet quality with insulin sensitivity and beta-cell function. | Size of Study Groups
296 | Lakka TA, Aittola K, Järvelä-Reijonen E, Tilles-Tirkkonen T, Männikkö R, Lintu N, Karhunen L, Kolehmainen M, Harjumaa M, Mattila E, Järvenpää R, Ermes M, Mikkonen S, Martikainen J, Poutanen K, Schwab U, Absetz P, Lindström J, Pihlajamäki J. Real-world effectiveness of digital and group-based lifestyle interventions as compared with usual care to reduce type 2 diabetes risk - A stop diabetes pragmatic randomised trial. 24. | Intervention/Exposure
297 | Lakka, TA, Lintu, N, Vaisto, J, Viitasalo, A, Sallinen, T, Haapala, EA, Tompuri, TT, Soininen, S, Karjalainen, P, Schnurr, TM, Mikkonen, S, Atalay, M, Kilpelainen, TO, Laitinen, T, Laaksonen, DE, Savonen, K, Brage, S, Schwab, U, Jaaskelainen, J, Lindi, V, Eloranta, AM. A 2 year physical activity and dietary intervention attenuates the increase in insulin resistance in a general population of children: the PANIC study. Diabetologia. 2020. 63:2270-2281. doi:10.1007/s00125-020-05250-0 | Intervention/Exposure
298 | Laouali, N, Berrandou, T, Rothwell J A, Shah, S, El Fatouhi, D, Romana Mancini, F, Boutron-Ruault, MC, Fagherazzi, G. Profiles of Polyphenol Intake and Type 2 Diabetes Risk in 60,586 Women Followed for 20 Years: Results from the E3N Cohort Study. Nutrients. 2020. 12. doi:10.3390/nu12071934 | Intervention/Exposure
299 | Lavie, M, Lavie, I, Maslovitz, S. Paleolithic diet during pregnancy-A potential beneficial effect on metabolic indices and birth weight. Eur J Obstet Gynecol Reprod Biol. 2019. 242:7-11. doi:10.1016/j.ejogrb.2019.08.013 | Study Design
300 | Lawrence, RL, Wall, CR, Bloomfield, FH. Adherence to Dietary Guidelines among Women with and without Gestational Diabetes: Evidence from the Growing Up in New Zealand Study. Nutrients. 2022. 14. | Study Design; Intervention/Exposure
301 | Lawrence, RL, Wall, CR, Bloomfield, FH. Dietary Patterns and Dietary Adaptations in Women with and without Gestational Diabetes: Evidence from the Growing Up in New Zealand Study. Nutrients. 2020. 12. doi:10.3390/nu12010227 | Study Design
302 | Lee KW, Shin D. Interactions between Bitter Taste Receptor Gene Variants and Dietary Intake Are Associated with the Incidence of Type 2 Diabetes Mellitus in Middle-Aged and Older Korean Adults. 24. | Intervention/Exposure
303 | Lee KW, Shin D. Positive association between dietary acid load and future insulin resistance risk: findings from the Korean Genome and Epidemiology Study. 19. | Intervention/Exposure
304 | Lee, DH, Fung, TT, Tabung, FK, Colditz, GA, Ghobrial, IM, Rosner, BA, Giovannucci, EL, Birmann, BM. Dietary Pattern and Risk of Multiple Myeloma in Two Large Prospective US Cohort Studies. JNCI cancer spectrum. 2019. 3:pkz025. | Outcome
305 | Lee, H-A, Park, H. Substitution of Carbohydrates for Fats and Risk of Type 2 Diabetes among Korean Middle-Aged Adults: Findings from the Korean Genome and Epidemiology Study. Nutrients. 2022. 14. | Intervention/Exposure
306 | Lehtovirta, Miia, Matthews, LaurieA, Laitinen, TomiT, Nuotio, Joel, Niinikoski, Harri, Rovio, SuviP, Lagström, Hanna, Viikari, JormaSA, Rönnemaa, Tapani, Jula, Antti, Ala-Korpela, Mika, Raitakari, OlliT, Pahkala, Katja, Demmelmair, Hans. Achievement of the Targets of the 20-Year Infancy-Onset Dietary Intervention—Association with Metabolic Profile from Childhood to Adulthood. Nutrients. 2021. 13:533-533. doi:10.3390/nu13020533 | Intervention/Exposure
307 | Levy, RenataB, Rauber, Fernanda, Chang, Kiara, Louzada, MariaLauradaC, Monteiro, CarlosA, Millett, Christopher, Vamos, EszterP. Ultra-processed food consumption and type 2 diabetes incidence: A prospective cohort study. Clinical Nutrition. 2021. 40:3608-3614. doi:10.1016/j.clnu.2020.12.018 | Intervention/Exposure
308 | Ley, SH, Chavarro, JE, Li, M, Bao, W, Hinkle, SN, Wander, PL, Rich-Edwards, J, Olsen, S, Vaag, A, Damm, P, Grunnet, LG, Mills, JL, Hu, FB, Zhang, C. Lactation Duration and Long-term Risk for Incident Type 2 Diabetes in Women With a History of Gestational Diabetes Mellitus. Diabetes Care. 2020. 43:793-798. doi:10.2337/dc19-2237 | Intervention/Exposure
309 | Li L, Shan Z, Wan Z, Li R, Geng T, Lu Q, Zhu K, Qiu Z, Zhang X, Liu Y, Liu L, Pan A, Liu G. Associations of lower-carbohydrate and lower-fat diets with mortality among people with prediabetes. | Study Design; Intervention/Exposure
310 | Li L, Wan Z, Geng T, Lu Q, Zhu K, Qiu Z, Zhang X, Liu Y, Tian Q, Liu L, Pan A, Shan Z, Liu G. Associations of healthy dietary patterns with mortality among people with prediabetes. | Study Design; Outcome
311 | Li Y, Yatsuya H, Wang C, Uemura M, Matsunaga M, He Y, Khine M, Ota A. Dietary Patterns Derived from Reduced Rank Regression Are Associated with the 5-Year Occurrence of Metabolic Syndrome: Aichi Workers’ Cohort Study. 14. | Outcome
312 | Li, LJ, Aris, IM, Han, WM, Tan, KH. A Promising Food-Coaching Intervention Program to Achieve Optimal Gestational Weight Gain in Overweight and Obese Pregnant Women: Pilot Randomized Controlled Trial of a Smartphone App. JMIR Form Res. 2019. 3:e13013. doi:10.2196/13013 | Intervention/Exposure; Outcome
313 | Li, M, Lin, Q, Shi, J, Xi, Y, Xiang, C, Yong, C, Guo, J. The impact of lifestyle intervention on dietary quality among rural women with previous gestational diabetes mellitus— a randomized controlled study. Nutrients. 2021. 13. | Outcome
314 | Li, M, Shi, Z. Association between Ultra-Processed Food Consumption and Diabetes in Chinese Adults—Results from the China Health and Nutrition Survey. Nutrients. 2022. 14. | Country
315 | Li, M, Li, S, Chavarro, JE, Gaskins, AJ, Ley, SH, Hinkle, SN, Wang, X, Ding, M, Bell, G, Bjerregaard, AA, Olsen, SF, Mills, JL, Hu, FB, Zhang, C. Prepregnancy habitual intakes of total, supplemental, and food folate and risk of gestational diabetes mellitus: A prospective cohort study. Diabetes Care. 2019. 42:1034-1041. doi:10.2337/dc18-2198 | Intervention/Exposure; Comparator
316 | Li, M, Rahman, ML, Wu, J, Ding, M, Chavarro, JE, Lin, Y, Ley, SH, Bao, W, Grunnet, LG, Hinkle, SN, Thuesen, ACB, Yeung, E, Gore-Langton, RE, Sherman, S, Hjort, L, Kampmann, FB, Bjerregaard, AA, Damm, P, Tekola-Ayele, F, Liu, A, Mills, JL, Vaag, A, Olsen, SF, Hu, FB, Zhang, C. Genetic factors and risk of type 2 diabetes among women with a history of gestational diabetes: findings from two independent populations. BMJ Open Diabetes Res Care. 2020. 8. doi:10.1136/bmjdrc-2019-000850 | Intervention/Exposure
317 | Li, M, Shi, J, Luo, J, Long, Q, Yang, Q, OuYang, Y, Liu, H, Lin, Q, Guo, J. Diet Quality among Women with Previous Gestational Diabetes Mellitus in Rural Areas of Hunan Province. Int J Environ Res Public Health. 2020. 17. doi:10.3390/ijerph17165942 | Health Status; Outcome
318 | Li, Y, Schoufour, J, Wang, DD, Dhana, K, Pan, A, Liu, X, Song, M, Liu, G, Shin, HJ, Sun, Q, Al-Shaar, L, Wang, M, Rimm, EB, Hertzmark, E, Stampfer, MJ, Willett, WC, Franco, OH, Hu, FB. Healthy lifestyle and life expectancy free of cancer, cardiovascular disease, and type 2 diabetes: prospective cohort study. BMJ. 2020. 368:l6669. doi:10.1136/bmj.l6669 | Outcome
319 | Liang, Z, Wang, L, Liu, H, Chen, Y, Zhou, T, Heianza, Y, Leng, J, Li, W, Yang, X, Shen, Y, Gao, R, Hu, G, Qi, L. Genetic susceptibility, lifestyle intervention and glycemic changes among women with prior gestational diabetes. Clin Nutr. 2020. 39:2144-2150. doi:10.1016/j.clnu.2019.08.032 | Intervention/Exposure
320 | Liedes H, Mattila E, Honka A, Absetz P, Aittola K, Manninen S, Lintu N, Schwab U, Eloranta AM, Umer A, Tilles-Tirkkonen T, Männikkö R, Ruotsalainen I, Van Gils M, Lindström J, Lakka T, Pihlajamäki J, Vuorinen AL. Associations Between Engagement with the BitHabit Digital Lifestyle Intervention and Changes in Type 2 Diabetes Risk Factors. 302. | Intervention/Exposure; Publication Status
321 | Lim, SX, Cox, V, Rodrigues, N, Colega, MT, Barton, SJ, Childs, CE, Conlon, CA, Wall, CR, Cutfield, WS, Chan, S-Y, Godfrey, KM, Chong, MF-F. Evaluation of Preconception Dietary Patterns in Women Enrolled in a Multisite Study. Current Developments in Nutrition. 2022. 6. | Study Design
322 | Lin, LY, Hsu, CY, Chiou, HY, Lee, HA, Hsu, LM, Chang, PY, Kurniawan, AL, Chao, JC. Association between Dietary Patterns and Serum Hepatic Enzyme Levels in Adults with Dyslipidemia and Impaired Fasting Plasma Glucose. Nutrients. 2021. 13. doi:10.3390/nu13030987 | Study Design; Outcome
323 | Lin, R, Chien, K-L, Tsai, M-C, Wang, Y-J, Hsu, L-Y. Association between a priori and a posteriori dietary patterns and the risk of type 2 diabetes: A representative cohort study in Taiwan. Journal of Nutritional Science. 2023. 12. | Country
324 | Lin, TJ, Tang, SC, Liao, PY, Dongoran, RA, Yang, JH, Liu, CH. A comparison of L-carnitine and several cardiovascular-related biomarkers between healthy vegetarians and omnivores. Nutrition. 2019. 66:29-37. doi:10.1016/j.nut.2019.03.019 | Study Design; Intervention/Exposure
325 | Lindsay KL, Most J, Buehler K, Kebbe M, Altazan AD, Redman LM. Maternal mindful eating as a target for improving metabolic outcomes in pregnant women with obesity. 26. | Intervention/Exposure
326 | Linke CS, Kelly J, Karlsen M, Pollard K, Trapp C. Type 2 Diabetes Prevention and Management With a Low-Fat, Whole-Food, Plant-Based Diet. 71. | Study Design
327 | Lisón, JF, Palomar, G, Mensorio, MS, Banõs, RM, Cebolla-Martí, A, Botella, C, Benavent-Caballer, V, Rodilla, E. Impact of a Web-Based Exercise and Nutritional Education Intervention in Patients Who Are Obese with Hypertension: Randomized Wait-List Controlled Trial. Journal of Medical Internet Research. 2020. 22. doi:10.2196/14196 | Intervention/Exposure
328 | Liu Q, Wen Q, Lv J, Shi Z, Guo Y, Pei P, Du H, Yang L, Chen Y, Zhang X, Schmidt D, Sansome S, Chen J, Yu C, Chen Z, Li L, On Behalf Of The China Kadoorie Biobank Ckb Collaborative Group. The Prospective Associations of Lipid Metabolism-Related Dietary Patterns with the Risk of Diabetes in Chinese Adults. 14. | Country
329 | Liu YH, Lu LP, Yi MH, Shen CY, Lu GQ, Jia J, Wu H. Study on the correlation between homocysteine-related dietary patterns and gestational diabetes mellitus:a reduced-rank regression analysis study. 22. | Study Design
330 | Liu, Mengyi, Liu, Chengzhang, Zhang, Zhuxian, Zhou, Chun, Li, Qinqin, He, Panpan, Zhang, Yuanyuan, Li, Huan, Qin, Xianhui. Quantity and variety of food groups consumption and the risk of diabetes in adults: A prospective cohort study. Clinical Nutrition. 2021. 40:5710-5717. doi:10.1016/j.clnu.2021.10.003 | Intervention/Exposure
331 | Liu, X, Zheng, Y, Guasch-Ferré, M, Ruiz-Canela, M, Toledo, E, Clish, C, Liang, L, Razquin, C, Corella, D, Estruch, R, Fito, M, Gómez-Gracia, E, Arós, F, Ros, E, Lapetra, J, Fiol, M, Serra-Majem, L, Papandreou, C, Martínez-González, MA, Hu, FB, Salas-Salvadó, J. High plasma glutamate and low glutamine-to-glutamate ratio are associated with type 2 diabetes: Case-cohort study within the PREDIMED trial. Nutrition, Metabolism and Cardiovascular Diseases. 2019. 29:1040-1049. doi:10.1016/j.numecd.2019.06.005 | Intervention/Exposure
332 | Livingstone KM, Milte CM, Torres SJ, Hart MJ, Dingle SE, Shaw JE, Magliano DJ, McNaughton SA. Nineteen-Year Associations between Three Diet Quality Indices and All-Cause and Cardiovascular Disease Mortality: The Australian Diabetes, Obesity, and Lifestyle Study. 152. | Outcome
333 | Lönnberg, L, Ekblom-Bak, E, Damberg, M. Improved unhealthy lifestyle habits in patients with high cardiovascular risk: results from a structured lifestyle programme in primary care. Upsala journal of medical sciences. 2019. 124:94-104. doi:10.1080/03009734.2019.1602088 | Study Design; Intervention/Exposure
334 | Lonnie M, Wadolowska L, Morze J, Bandurska-Stankiewicz E. Associations of Dietary-Lifestyle Patterns with Obesity and Metabolic Health: Two-Year Changes in MeDiSH(®) Study Cohort. 19. | Intervention/Exposure; Comparator
335 | Looman, M, Geelen, A, Samlal, RAK, Heijligenberg, R, Klein Gunnewiek, JMT, Balvers, MGJ, Wijnberger, LDE, Brouwer-Brolsma, EM, Feskens, EJM. Changes in micronutrient intake and status, diet quality and glucose tolerance from preconception to the second trimester of pregnancy. Nutrients. 2019. 11. doi:10.3390/nu11020460 | Data Overlap
336 | Lopez-Contreras, IN, Vilchis-Gil, J, Klunder-Klunder, M, Villalpando-Carrion, S, Flores-Huerta, S. Dietary habits and metabolic response improve in obese children whose mothers received an intervention to promote healthy eating: randomized clinical trial. BMC Public Health. 2020. 20:1240. doi:10.1186/s12889-020-09339-4 | Intervention/Exposure
337 | Lopez-Olmedo, N, Jonnalagadda, S, Basto-Abreu, A, Reyes-Garcia, A, Alish, CJ, Shamah-Levy, T, Barrientos-Gutierrez, T. Adherence to Dietary Guidelines in Adults by Diabetes Status: Results From the 2012 Mexican National Health and Nutrition Survey. Nutrients. 2020. 12. doi:10.3390/nu12113464 | Study Design
338 | Lotfaliany, M, Mansournia, MA, Azizi, F, Hadaegh, F, Zafari, N, Ghanbarian, A, Mirmiran, P, Oldenburg, B, Khalili, D. Long-term effectiveness of a lifestyle intervention on the prevention of type 2 diabetes in a middle-income country. Sci Rep. 2020. 10:14173. doi:10.1038/s41598-020-71119-2 | Intervention/Exposure
339 | Lotfi, MH, Fallahzadeh, H, Rahmanian, M, Hosseinzadeh, M, Lashkardoost, H, Doaei, S, Gholamalizadeh, M, Hamedi, A. Association of food groups intake and physical activity with gestational diabetes mellitus in Iranian women. J Matern Fetal Neonatal Med. 2020. 33:3559-3564. doi:10.1080/14767058.2019.1579189 | Study Design
340 | Lowe, DA, Wu, N, Rohdin-Bibby, L, Moore, AH, Kelly, N, Liu, YE, Philip, E, Vittinghoff, E, Heymsfield, SB, Olgin, JE, Shepherd, JA, Weiss, EJ. Effects of Time-Restricted Eating on Weight Loss and Other Metabolic Parameters in Women and Men with Overweight and Obesity: The TREAT Randomized Clinical Trial. JAMA Internal Medicine. 2020. 180:1491-1499. doi:10.1001/jamainternmed.2020.4153 | Intervention/Exposure
341 | Lu, D, Yuan, Z, Yang, L, Jiang, Y, Li, M, Wang, Y, Jing, L, Wang, R, Zhang, J, Guo, X. Body Composition and Metabolic Improvement in Patients Followed up by a Multidisciplinary Team for Obesity in China. Journal of Diabetes Research. 2021. 2021. | Intervention/Exposure
342 | Luo Y, Wang J, Sun L, Gu W, Zong G, Song B, Shen C, Zhou P, Chen Y, Wu Y, Lin H, Zheng H, Ni M, Yang X, Chen Y, Xu X, Zhang J, Shi J, Zhang R, Hu J, Hou H, Lu L, Xu X, Liang L, Liu R, Liu X, Li H, Hong J, Wang W, Lin X, Ning G. Isocaloric-restricted Mediterranean diet and Chinese diets high or low in plants in adults with prediabetes. | Outcome
343 | Lüscher, TF. Nutrition, obesity, diabetes, and cardiovascular outcomes: A deadly association. European Heart Journal. 2020. 41:2603-2607. doi:10.1093/eurheartj/ehaa622 | Publication Status
344 | Lynch, EB, Mack, L, Avery, E, Wang, Y, Dawar, R, Richardson, DJ, Keim, K, Ventrelle, J, Appelhans, BM, Tahsin, B, Fogelfeld, L. Randomized Trial of a Lifestyle Intervention for Urban Low-Income African Americans with Type 2 Diabetes. Journal of General Internal Medicine. 2019. 34:1174-1183. doi:10.1007/s11606-019-04894-y | Intervention/Exposure; Health Status
345 | Madlala SS, Hill J, Kunneke E, Kengne AP, Peer N, Faber M. Dietary Diversity and its Association with Nutritional Status, Cardiometabolic Risk Factors and Food Choices of Adults at Risk for Type 2 Diabetes Mellitus in Cape Town, South Africa. 14. | Study Design
346 | Magkos F, Rasmussen SI, Hjorth MF, Asping S, Rosenkrans MI, Sjödin AM, Astrup AV, Geiker NRW. Unprocessed red meat in the dietary treatment of obesity: a randomized controlled trial of beef supplementation during weight maintenance after successful weight loss. | Intervention/Exposure
347 | Mahdavi S, Jenkins DJA, El-Sohemy A. Genetic variation in 9p21, dietary patterns, and insulin sensitivity. 13. | Study Design; Comparator
348 | Mahjoub, F, Ben Jemaa, H, Ben Sabeh, F, Ben Amor, N, Gamoudi, A, Jamoussi, H. Impact of nutrients and Mediterranean diet on the occurrence of gestational diabetes. Libyan Journal of Medicine. 2021. 16. doi:10.1080/19932820.2021.1930346 | Study Design
349 | Mahmoudinezhad M, Abbasalizad Farhangi M. Association between Ag-RP, alpha-MSH and cardiovascular risk factors regarding adherence to diet quality index-international (DQI-I) among obese individuals. 13. | Study Design
350 | Mak, JKL, Pham, NM, Lee, AH, Tang, L, Pan, X-F, Binns, CW, Sun, X. Dietary patterns during pregnancy and risk of gestational diabetes: A prospective cohort study in Western China. Nutrition Journal. 2018. 17. | Data Overlap
351 | Maldonado LE, Farzan SF, Toledo-Corral CM, Dunton GF, Habre R, Eckel SP, Johnson M, Yang T, Grubbs BH, Lerner D, Chavez T, Breton CV, Bastain TM. A Vegetable, Oil, and Fruit Dietary Pattern in Late Pregnancy is Linked to Reduced Risks of Adverse Birth Outcomes in a Predominantly Low-Income Hispanic and Latina Pregnancy Cohort. 152. | Study Design; Outcome
352 | Maldonado LE, Farzan SF, Toledo-Corral CM, Dunton GF, Habre R, Eckel SP, Johnson M, Yang T, Grubbs BH, Lerner D, Chavez T, Breton CV, Bastain TM. A Vegetables, Oils, and Fruit Dietary Pattern in Late Pregnancy is Linked to Reduced Risk of Adverse Birth Outcomes in a Predominantly Low-Income Hispanic/Latina Pregnancy Cohort. | Study Design
353 | Mancioppi, V, Solito, A, Ricotti, R, Carrera, D, Archero, F, Landoni, V, Errichiello, R, Bona, E, Cavaletto, M, Bellone, S, etal, . Good-day: efficacy of gamification of an educational training to mediterranean diet on weight and metabolic control in paediatric obesity. preliminary data at 6 months. High blood pressure & cardiovascular prevention. 2019. 26:171-172. doi:10.1007/s40292-019-00308-6 | Publication Status
354 | Mansourian, M, Yazdani, A, Faghihimani, E, Aminorraya, A, Amini, M, Jafari-Koshki, T. Factors associated with progression to pre-diabetes: a recurrent events analysis. Eating and Weight Disorders. 2020. 25:135-141. doi:10.1007/s40519-018-0529-7 | Study Design; Intervention/Exposure
355 | Martensson, A, Stomby, A, Tellstrom, A, Ryberg, M, Waling, M, Otten, J. Using a Paleo Ratio to Assess Adherence to Paleolithic Dietary Recommendations in a Randomized Controlled Trial of Individuals with Type 2 Diabetes. Nutrients. 2021. 13. doi:10.3390/nu13030969 | Intervention/Exposure; Health Status
356 | Martin, S, Banzer, W, Berg, A, Braumann, KM, Fuhrer, D, Halle, M, McCarthy, D, Pinget, M, Predel, G, Toplak, H. Prediabetes conversion to normoglycemia is superior adding a low-carbohydrate formula diet to lifestyle intervention-a 12-month subanalysis of the accorh study. Diabetes. 2019. 68. doi:10.2337/db19-327-OR | Publication Status
357 | Martinez-Gonzalez, MA, Fernandez-Lazaro, CI, Toledo, E, Diaz-Lopez, A, Corella, D, Goday, A, Romaguera, D, Vioque, J, Alonso-Gomez, AM, Warnberg, J, Martinez, JA, Serra-Majem, L, Estruch, R, Tinahones, FJ, Lapetra, J, Pinto, X, Tur, JA, Lopez-Miranda, J, Cano-Ibanez, N, Delgado-Rodriguez, M, Matia-Martin, P, Daimiel, L, Sanchez, VM, Vidal, J, Vazquez, C, Ros, E, Buil-Cosiales, P, Portoles, O, Soria-Florido, M, Konieczna, J, Navarrete-Munoz, EM, Tojal-Sierra, L, Fernandez-Garcia, JC, Abete, I, Henriquez-Sanchez, P, Munoz-Garach, A, Santos-Lozano, JM, Corbella, E, Bibiloni, MDM, Becerra-Tomas, N, Barragan, R, Castaner, O, Fiol, M, Garcia de la Hera, M, Bello-Mora, MC, Gea, A, Babio, N, Fito, M, Ruiz-Canela, M, Zazpe, I, Salas-Salvado, J. Carbohydrate quality changes and concurrent changes in cardiovascular risk factors: a longitudinal analysis in the PREDIMED-Plus randomized trial. Am J Clin Nutr. 2020. 111:291-306. doi:10.1093/ajcn/nqz298 | Intervention/Exposure
358 | Martin-Piedra L, Alcala-Diaz JF, Gutierrez-Mariscal FM, Arenas de Larriva AP, Romero-Cabrera JL, Torres-Peña JD, Caballero-Villarraso J, Luque RM, Perez-Martinez P, Lopez-Miranda J, Delgado-Lista J. Evolution of Metabolic Phenotypes of Obesity in Coronary Patients after 5 Years of Dietary Intervention: From the CORDIOPREV Study. 13. | Health Status
359 | Maskarinec, G, Hullar, MAJ. Understanding the Interaction of Diet Quality with the Gut Microbiome and Their Effect on Disease. J Nutr. 2020. 150:654-655. doi:10.1093/jn/nxaa015 | Outcome; Publication Status
360 | Mattavelli E, Olmastroni E, Casula M, Grigore L, Pellegatta F, Baragetti A, Magni P, Catapano AL. Adherence to Mediterranean Diet: A Population-Based Longitudinal Cohort Study. 15. | Size of Study Groups
361 | Mauro, Antonio Di, Tuccinardi, Dario, Toro, Rossella Del, Monte, Lavinia, Giorgino, Riccardo, Rampa, Lorenzo, Rossini, Giovanni, Kyanvash, Shadi, Soare, Andreea, Rosati, MilenaM, Khazrai, Yeganeh Manon, Piccoli, Alessandra, Napoli, Nicola, Pozzilli, Paolo, Manfrini, Silvia. 226-OR: The Mediterranean Diet Increases GLP-1 and Oxyntomodulin Compared with Vegetarian Diet in Type 2 Diabetes Subjects. Diabetes. 2020. 69. doi:10.2337/db20-226-OR | Publication Status
362 | Mazidi, M, Katsiki, N, Mikhailidis, DP, Banach, M. Effect of Dietary Insulinemia on All-Cause and Cause-Specific Mortality: Results From a Cohort Study. Journal of the American College of Nutrition. 2020. 39:407-413. doi:10.1080/07315724.2019.1646167 | Outcome
363 | Mazidi, M, Katsiki, N, Mikhailidis, DP, Bartłomiejczyk, MA, Banach, M. Association of empirical dietary atherogenic indices with all-cause and cause-specific mortality in a multi-ethnic adult population of the United States. Nutrients. 2019. 11. doi:10.3390/nu11102323 | Intervention/Exposure; Outcome
364 | McEvoy, CT, Moore, SE, Erwin, CM, Kontogianni, M, Wallace, SM, Appleton, KM, Cupples, ME, Hunter, SJ, Kee, F, McCance, D, Patterson, CC, Young, IS, McKinley, MC, Woodside, JV. Trial to Encourage Adoption and Maintenance of a MEditerranean Diet (TEAM-MED): a randomised pilot trial of a peer support intervention for dietary behaviour change in adults from a Northern European population at high cardiovascular disease risk. The British journal of nutrition. 2021. 1. | Intervention/Exposure; Size of Study Groups
365 | McKenzie, AL, Athinarayanan, SJ, McCue, JJ, Adams, RN, Keyes, M, McCarter, JP, Volek, JS, Phinney, SD, Hallberg, SJ. Type 2 diabetes prevention focused on normalization of glycemia: A two-year pilot study. Nutrients. 2021. 13:1-9. doi:10.3390/nu13030749 | Study Design; Intervention/Exposure
366 | Mei S, Ding J, Wang K, Ni Z, Yu J. Mediterranean Diet Combined With a Low-Carbohydrate Dietary Pattern in the Treatment of Overweight Polycystic Ovary Syndrome Patients. 9. | Intervention/Exposure
367 | Meinila, J, Valkama, A, Koivusalo, SB, Rönö, K, Kautiainen, H, Lindström, J, Stach-Lempinen, B, Eriksson, JG, Erkkola, M. Association between diet quality measured by the Healthy Food Intake Index and later risk of gestational diabetes - A secondary analysis of the RADIEL trial. European Journal of Clinical Nutrition. 2017. 71:555. | Data Overlap
368 | Melero, V, Assaf-Balut, C, Torre, NG, Jimenez, I, Bordiu, E, Valle, LD, Valerio, J, Familiar, C, Duran, A, Runkle, I, Miguel, MP, Montanez, C, Barabash, A, Cuesta, M, Herraiz, MA, Izquierdo, N, Rubio, MA, Calle-Pascual, AL. Benefits of Adhering to a Mediterranean Diet Supplemented with Extra Virgin Olive Oil and Pistachios in Pregnancy on the Health of Offspring at 2 Years of Age. Results of the San Carlos Gestational Diabetes Mellitus Prevention Study. J Clin Med. 2020. 9. doi:10.3390/jcm9051454 | Data Overlap
369 | Menichini, D, Petrella, E, Dipace, V, Di Monte, A, Neri, I, Facchinetti, F. The Impact of an Early Lifestyle Intervention on Pregnancy Outcomes in a Cohort of Insulin-Resistant Overweight and Obese Women. Nutrients. 2020. 12. doi:10.3390/nu12051496 | Intervention/Exposure; Comparator
370 | Merino, J, Jablonski, KA, Mercader, JM, Kahn, SE, Chen, L, Harden, M, Delahanty, LM, Araneta, MRG, Walford, GA, Jacobs, SBR, Ibebuogu, UN, Franks, PW, Knowler, WC, Florez, JC, Diabetes Prevention Program Research, Group. Interaction Between Type 2 Diabetes Prevention Strategies and Genetic Determinants of Coronary Artery Disease on Cardiometabolic Risk Factors. Diabetes. 2020. 69:112-120. doi:10.2337/db19-0097 | Intervention/Exposure
371 | Meroni, A, Muirhead, RP, Atkinson, FS, Fogelholm, M, Raben, A, Brand-Miller, JC. Is a Higher Protein-Lower Glycemic Index Diet More Nutritious Than a Conventional Diet? A PREVIEW Sub-study. Front Nutr. 2020. 7:603801. doi:10.3389/fnut.2020.603801 | Intervention/Exposure
372 | Migliaretti, G, Ame, C, Ciullo, S, Fontana, E, Stura, I, Nano, E, Laino, F, Isoardo, G. Metabolic and psychological effects of short-term increased consumption of less-processed foods in daily diets: A Pilot Study. Diabetes and Metabolism. 2020. 46:66. | Intervention/Exposure
373 | Miller CK, King D, Nagaraja HN, Fujita K, Cheavens J, Focht BC. Impact of an augmented intervention on self-regulatory, dietary and physical activity outcomes in a diabetes prevention trial among adults with prediabetes. | Intervention/Exposure
374 | Milone, Gina, Chung, JudithH, Haas, DavidM, Silver, RobertM, Grobman, WilliamA, Simhan, Hyagriv, Saade, GeorgeR, Reddy, UmaM, Lindsay, Karen. Periconceptional diet quality predicts glycemic control and gestational diabetes risk in nulliparous women. American Journal of Obstetrics & Gynecology. 2022. 226:S46-S47. doi:10.1016/j.ajog.2021.11.106 | Publication Status
375 | Minhas, AS, Hong, X, Wang, G, Rhee, DK, Liu, T, Zhang, M, Michos, ED, Wang, X, Mueller, NT. Mediterranean-Style Diet and Risk of Preeclampsia by Race in the Boston Birth Cohort. Journal of the American Heart Association. 2022. 11. | Study Design
376 | Mirmiran P, Hosseini S, Bahadoran Z, Azizi F. Dietary pattern scores in relation to pre-diabetes regression to normal glycemia or progression to type 2 diabetes: a 9-year follow-up. 23. | Size of Study Groups
377 | Mirmiran P, Ramezan M, Farhadnejad H, Asghari G, Tahmasebinejad Z, Azizi F. High Dietary Diabetes Risk Reduction Score Is Associated with Decreased Risk of Chronic Kidney Disease in Tehranian Adults. 2022. | Study Design; Outcome
378 | Mirmiran, P, Hosseinpour-Niazi, S, Moghaddam-Banaem, L, Lamyian, M, Goshtasebi, A, Azizi, F. Inverse relation between fruit and vegetable intake and the risk of gestational diabetes mellitus. International Journal for Vitamin and Nutrition Research. 2019. 89:37-44. doi:10.1024/03009831/a000475 | Intervention/Exposure
379 | Mirmiran, P, Ziadlou, M, Karimi, S, Hosseini-Esfahani, F, Azizi, F. The association of dietary patterns and adherence to WHO healthy diet with metabolic syndrome in children and adolescents: Tehran lipid and glucose study. BMC Public Health. 2019. 19:1457. doi:10.1186/s12889-019-7779-9 | Outcome
380 | Mitchell, A, Fall, T, Melhus, H, Wolk, A, Michaelsson, K, Byberg, L. Is the effect of Mediterranean diet on hip fracture mediated through type 2 diabetes mellitus and body mass index?. Int J Epidemiol. 2021. 50:234-244. doi:10.1093/ije/dyaa239 | Outcome
381 | Mitra, SR, Tan, PY. Effect of an individualised high-protein, energy-restricted diet on anthropometric and cardio-metabolic parameters in overweight and obese Malaysian adults: A 6-month randomised controlled study. British Journal of Nutrition. 2019. 121:1002-1017. doi:10.1017/S0007114519000345 | Intervention/Exposure
382 | Mizgier, M, Jarzabek-Bielecka, G, Mruczyk, K. Maternal diet and gestational diabetes mellitus development. J Matern Fetal Neonatal Med. 2021. 34:77-86. doi:10.1080/14767058.2019.1598364 | Intervention/Exposure
383 | Mohd Yusof, BN. A low glycemic index diet in the management of gestational diabetes mellitus: the Malaysian experience. Annals of nutrition & metabolism. 2019. 75:34-35. doi:10.1159/000501751 | Publication Status
384 | Mokhtari, E, Farhadnejad, H, Teymoori, F, Mirmiran, P, Azizi, F. The association of insulinemic potential of diet and lifestyle with the risk of insulin-related disorders: a prospective cohort study among participants of Tehran Lipid and Glucose Study. Diabetology and Metabolic Syndrome. 2021. 13. | Outcome
385 | Molina-Leyva, A, Cuenca-Barrales, C, Vega-Castillo, JJ, Ruiz-Carrascosa, JC, Ruiz-Villaverde, R. Adherence to Mediterranean diet in Spanish patients with psoriasis: Cardiovascular benefits?. Dermatologic Therapy. 2019. 32. doi:10.1111/dth.12810 | Study Design; Health Status
386 | Montemayor S, Mascaró CM, Ugarriza L, Casares M, Llompart I, Abete I, Zulet MÁ, Martínez JA, Tur JA, Bouzas C. Adherence to Mediterranean Diet and NAFLD in Patients with Metabolic Syndrome: The FLIPAN Study. 14. | Outcome
387 | Mu, L, Yu, P, Xu, H, Gong, T, Chen, D, Tang, J, Zou, Y, Rao, H, Mei, Y, Mu, L. Efecto de la reducción de sodio basada en la dieta DASH sobre la presión arterial en pacientes hipertensos con diabetes de tipo 2. Effect of sodium reduction based on the DASH diet on blood pressure in hypertensive patients with type 2 diabetes. 2022. | Health Status
388 | Mulcahy MC, Tellez-Rojo MM, Cantoral A, Solano-González M, Baylin A, Bridges D, Peterson KE, Perng W. Maternal Carbohydrate Intake During Pregnancy is Associated with Child Peripubertal Markers of Metabolic Health but not Adiposity. | Intervention/Exposure
389 | Muralidharan J, Moreno-Indias I, Bulló M, Lopez JV, Corella D, Castañer O, Vidal J, Atzeni A, Fernandez-García JC, Torres-Collado L, Fernández-Carrión R, Fito M, Olbeyra R, Gomez-Perez AM, Galiè S, Bernal-López MR, Martinez-Gonzalez MA, Salas-Salvadó J, Tinahones FJ. Effect on gut microbiota of a 1-y lifestyle intervention with Mediterranean diet compared with energy-reduced Mediterranean diet and physical activity promotion: PREDIMED-Plus Study. 114. | Intervention/Exposure
390 | Murni IK, Sulistyoningrum DC, Susilowati R, Julia M, Dickinson KM. The association between dietary intake and cardiometabolic risk factors among obese adolescents in Indonesia. 22. | Study Design
391 | Murphy, J. Exercise, healthy diet in midlife may prevent serious health conditions in senior years. Pharmacy Times. 2021. 89. | Publication Status
392 | Murphy, KJ, Dyer, KA, Hyde, B, Davis, CR, Bracci, EL, Woodman, RJ, Hodgson, JM. Long-Term Adherence to a Mediterranean Diet 1-Year after Completion of the MedLey Study. Nutrients. 2022. 14. | Outcome
393 | Muscogiuri, G, Barrea, L, Di Somma, C, Altieri, B, Vecchiarini, M, Orio, F, Spinosa, T, Colao, A, Savastano, S. Patient empowerment and the Mediterranean diet as a possible tool to tackle prediabetes associated with overweight or obesity: a pilot study. Hormones. 2019. 18:75-84. doi:10.1007/s42000-018-0090-9 | Study Design; Comparator
394 | Mustafa, S, Harding, J, Wall, C, Crowther, C. Sociodemographic factors associated with adherence to dietary guidelines in women with gestational diabetes: A cohort study. Nutrients. 2021. 13. | Health Status
395 | Myshak-Davis AT, Evans J, Howay H, Sakakibara BM. The effects of a primary care low-carbohydrate, high-fat dietary educational intervention on laboratory and anthropometric data of patients with chronic disease: a retrospective cohort chart review. | Study Design; Intervention/Exposure
396 | Nabila S, Kim JE, Choi J, Park J, Shin A, Lee SA, Lee JK, Kang D, Choi JY. Associations Between Modifiable Risk Factors and Changes in Glycemic Status Among Individuals With Prediabetes. | Intervention/Exposure; Publication Status
397 | Nah, EH, Chu, J, Kim, S, Cho, S, Kwon, E. Efficacy of lifestyle interventions in the reversion to normoglycemia in Korean prediabetics: One-year results from a randomised controlled trial. Primary Care Diabetes. 2019. 13:212-220. doi:10.1016/j.pcd.2018.11.017 | Intervention/Exposure
398 | Nct, . A Mediterranean Intervention on Prediabetic Children. https://clinicaltrials.gov/show/NCT05424107. 2022. | Publication Status
399 | Nct, . Acceptability, Feasibility and Effectiveness of a Worksite Intervention to Lower Cardiometabolic Risk in South Africa. https://clinicaltrials.gov/show/NCT04494139. 2020. | Publication Status
400 | Nct, . Healthy Lifestyle Intervention on Diabetes Risk Reduction Among Bruneian Young Adults. https://clinicaltrials.gov/show/NCT04217759. 2020. | Publication Status
401 | Nct, . Optimizing Gestational Weight Gain for Prevention of Gestational Diabetes Mellitus in Malaysia. https://clinicaltrials.gov/show/NCT05489536. 2022. | Publication Status
402 | Nguyen, Hai Duc, Oh, Hojin, Kim, Min-Sun. Higher intakes of fruits, vegetables, and multiple individual nutrients is associated with a lower risk of metabolic syndrome among adults with comorbidities. Nutrition Research. 2022. 99:1-12. doi:10.1016/j.nutres.2021.11.004 | Study Design; Intervention/Exposure
403 | Nilsen, I, Andersson, A, Laurenius, A, Osterberg, J, Sundbom, M, Haenni, A. Lower interstitial glucose concentrations but higher glucose variability during low-energy diet compared to regular diet—an observational study in females with obesity. Nutrients. 2021. 13. | Intervention/Exposure; Study Duration
404 | Njike VY, Kela GCM, Treu JA, Ayettey RG, Kussaga FM, Khan N, Comerford B, Agboola O. Egg Consumption in the Context of Plant-Based Diets and Diet Quality in Adults at Risk for Type 2 Diabetes: A Randomized Single Blind Cross-over Controlled Trial. | Study Duration; Outcome
405 | Njike, VY, Treu, JA, Kela, GCM, Ayettey, RG, Comerford, BP, Siddiqui, WT. Egg Consumption in the Context of Plant-Based Diets and Cardiometabolic Risk Factors in Adults at Risk of Type 2 Diabetes. The Journal of nutrition. 2021. | Intervention/Exposure; Study Duration
406 | Nouri, F, Sadeghi, M, Mohammadifard, N, Roohafza, H, Feizi, A, Sarrafzadegan, N. Longitudinal association between an overall diet quality index and latent profiles of cardiovascular risk factors: results from a population based 13-year follow up cohort study. Nutr Metab (Lond). 2021. 18:28. doi:10.1186/s12986-021-00560-5 | Outcome; Country
407 | O’Brien, EC, Geraghty, AA, O’Sullivan, EJ, Riordan, JA, Horan, MK, Larkin, E, Donnelly, J, Mehegan, J, Twomey, PJ, McAuliffe, FM. Five-year follow up of a low glycaemic index dietary randomised controlled trial in pregnancy—no long-term maternal effects of a dietary intervention. BJOG: An International Journal of Obstetrics and Gynaecology. 2019. 126:514-524. doi:10.1111/1471-0528.15500 | Intervention/Exposure; Outcome
408 | O’Hearn M, Erndt-Marino J, Gerber S, Lauren BN, Economos C, Wong JB, Blumberg JB, Mozaffarian D. Validation of Food Compass with a healthy diet, cardiometabolic health, and mortality among U.S. adults, 1999-2018. 13. | Outcome
409 | Okuda M, Fujiwara A, Sasaki S. Adherence to the Japanese Food Guide: The Association between Three Scoring Systems and Cardiometabolic Risks in Japanese Adolescents. 14. | Study Design
410 | Oliverio, A, Radice, P, Colombo, M, Paradiso, A, Tommasi, S, Daniele, A, Terribile, DA, Magno, S, Guarino, D, Manoukian, S, Peissel, B, Bruno, E, Pasanisi, P. The Impact of Mediterranean Dietary Intervention on Metabolic and Hormonal Parameters According to BRCA1/2 Variant Type. Frontiers in Genetics. 2022. 13. | Intervention/Exposure; Comparator
411 | Olsson, K, Ramne, S, Gonzalez-Padilla, E, Ericson, U, Sonestedt, E. Associations of carbohydrates and carbohydrate-rich foods with incidence of type 2 diabetes. Br J Nutr. 2021. 126:1065-1075. doi:10.1017/S0007114520005140 | Intervention/Exposure
412 | O’Reilly, S, Versace, V, Mohebbi, M, Lim, S, Janus, E, Dunbar, J. The effect of a diabetes prevention program on dietary quality in women with previous gestational diabetes. BMC Women’s Health. 2019. 19. doi:10.1186/s12905-019-0788-0 | Comparator
413 | Otten, J, Ryberg, M, Mellberg, C, Andersson, T, Chorell, E, Lindahl, B, Larsson, C, Holst, JJ, Olsson, T. Postprandial levels of GLP-1, GIP and glucagon after 2 years of weight loss with a Paleolithic diet: A randomised controlled trial in healthy obese women. European Journal of Endocrinology. 2019. 180:417-427. doi:10.1530/EJE-19-0082 | Intervention/Exposure; Outcome
414 | Øyen, J, Brantsæter, AL, Nøstbakken, OJ, Birkeland, KI, Haugen, M, Madsen, L, Egeland, GM. Intakes of Fish and Long-chain n-3 Polyunsaturated Fatty Acid Supplements During Pregnancy and Subsequent Risk of Type 2 Diabetes in a Large Prospective Cohort Study of Norwegian Women. Diabetes care. 2021. | Intervention/Exposure
415 | Pactr, . Impact of adding high probiotic food supplements to the diet and yoga on insulin resistance in polycystic ovarian syndrome. https://trialsearch.who.int/Trial2.aspx?TrialID=PACTR202211578683612. 2022. | Health Status; Publication Status
416 | Pahkala, K, Laitinen, TT, Niinikoski, H, Kartiosuo, N, Rovio, SP, Lagstrom, H, Loo, BM, Salo, P, Jokinen, E, Magnussen, CG, Juonala, M, Simell, O, Jula, A, Ronnemaa, T, Viikari, J, Raitakari, OT. Effects of 20-year infancy-onset dietary counselling on cardiometabolic risk factors in the Special Turku Coronary Risk Factor Intervention Project (STRIP): 6-year post-intervention follow-up. Lancet Child Adolesc Health. 2020. 4:359-369. doi:10.1016/S2352-4642(20)30059-6 | Intervention/Exposure
417 | Paik, JK, Park, M, Shin, JE, Jang, SY, Shin, JY. Dietary Protein to Carbohydrate Ratio and Incidence of Metabolic Syndrome in Korean Adults Based on a Long-Term Prospective Community-Based Cohort. Nutrients. 2020. 12. doi:10.3390/nu12113274 | Intervention/Exposure
418 | Päivärinta, E, Itkonen, ST, Pellinen, T, Lehtovirta, M, Erkkola, M, Pajari, AM. Replacing animal-based proteins with plant-based proteins changes the composition of a whole nordic diet—a randomised clinical trial in healthy Finnish adults. Nutrients. 2020. 12. doi:10.3390/nu12040943 | Intervention/Exposure; Outcome
419 | Palmer, Rachel. Mediterranean Diet During Pregnancy May Reduce Risk of Metabolic Syndrome. Scan’s Pulse. 2021. 41:21-21. | Publication Status
420 | Paltoglou G, Raftopoulou C, Nicolaides NC, Genitsaridi SM, Karampatsou SI, Papadopoulou M, Kassari P, Charmandari E. A Comprehensive, Multidisciplinary, Personalized, Lifestyle Intervention Program Is Associated with Increased Leukocyte Telomere Length in Children and Adolescents with Overweight and Obesity. 13. | Intervention/Exposure
421 | Pan W, Karatela S, Lu Q, Xie L, Wu S, Jing J, Cai L. Association of Diet Quality during Pregnancy with Maternal Glucose Metabolism in Chinese Women. | Size of Study Groups
422 | Pandya R, Abdelaal R, Chen JW, Masood S, Talib Z, Atamna H, Yakub M, Hassan SS. Retrospective assessment of metabolic syndrome components in early adult life on vegetarian dietary status. 10. | Intervention/Exposure
423 | Panizza, CE, Lim, U, Yonemori, KM, Cassel, KD, Wilkens, LR, Harvie, MN, Maskarinec, G, Delp, EJ, Lampe, JW, Shepherd, JA, Le Marchand, L, Boushey, CJ. Effects of intermittent energy restriction combined with a mediterranean diet on reducing visceral adiposity: A randomized active comparator pilot study. Nutrients. 2019. 11. doi:10.3390/nu11061386 | Intervention/Exposure; Outcome
424 | Papandreou P, Gioxari A, Daskalou E, Grammatikopoulou MG, Skouroliakou M, Bogdanos DP. Mediterranean Diet and Physical Activity Nudges versus Usual Care in Women with Rheumatoid Arthritis: Results from the MADEIRA Randomized Controlled Trial. 15. | Health Status; Outcome
425 | Park S. A Causal and Inverse Relationship between Plant-Based Diet Intake and in a Two-Sample Mendelian Randomization Study. 12. | Study Design
426 | Park S. Association of polygenic risk scores for insulin resistance risk and their interaction with a plant-based diet, especially fruits, vitamin C, and flavonoid intake, in Asian adults. 111. | Study Design; Intervention/Exposure
427 | Park S. Interaction of Polygenetic Variants for Gestational Diabetes Mellitus Risk with Breastfeeding and Korean Balanced Diet to Influence Type 2 Diabetes Risk in Later Life in a Large Hospital-Based Cohort. 11. | Study Design; Intervention/Exposure
428 | Park, YMM, Choi, MK, Lee, SS, Shivappa, N, Han, K, Steck, SE, Hébert, JR, Merchant, AT, Sandler, DP. Dietary inflammatory potential and risk of mortality in metabolically healthy and unhealthy phenotypes among overweight and obese adults. Clinical Nutrition. 2019. 38:682-688. doi:10.1016/j.clnu.2018.04.002 | Intervention/Exposure; Outcome
429 | Parlapani, E, Agakidis, C, Karagiozoglou-Lampoudi, T, Sarafidis, K, Agakidou, E, Athanasiadis, A, Diamanti, E. The Mediterranean diet adherence by pregnant women delivering prematurely: association with size at birth and complications of prematurity. Journal of Maternal-Fetal and Neonatal Medicine. 2019. 32:1084-1091. doi:10.1080/14767058.2017.1399120 | Study Design
430 | Parnell LD, Noel SE, Bhupathiraju SN, Smith CE, Haslam DE, Zhang X, Tucker KL, Ordovas JM, Lai CQ. Metabolite patterns link diet, obesity, and type 2 diabetes in a Hispanic population. 17. | Intervention/Exposure
431 | Partula, Valentin, Deschasaux, Mélanie, Druesne-Pecollo, Nathalie, Latino-Martel, Paule, Desmetz, Elisa, Chazelas, Eloi, Kesse-Guyot, Emmanuelle, Julia, Chantal, Fezeu, LéopoldK, Galan, Pilar, Hercberg, Serge, Mondot, Stanislas, Lantz, Olivier, Quintana-Murci, Lluis, Albert, MatthewL, Duffy, Darragh, Consortium, The Milieu Intérieur, Srour, Bernard, Touvier, Mathilde. Associations between consumption of dietary fibers and the risk of cardiovascular diseases, cancers, type 2 diabetes, and mortality in the prospective NutriNet-Santé cohort. American Journal of Clinical Nutrition. 2020. 112:195-207. doi:10.1093/ajcn/nqaa063 | Intervention/Exposure
432 | Peacock, L, Seed, PT, Dalrymple, KV, White, SL, Poston, L, Flynn, AC. The UK Pregnancies Better Eating and Activity Trial (UPBEAT); Pregnancy Outcomes and Health Behaviours by Obesity Class. Int J Environ Res Public Health. 2020. 17. doi:10.3390/ijerph17134712 | Intervention/Exposure
433 | Peng S, Yu Y, Yu X, Guo D, Su L, Li H, Luo P, Chen P, Wu S, Huang Y, Zhao Y, Fang A. Adherence to the Chinese dietary guidelines and metabolic syndrome among children aged 6-14 years. 13. | Study Design
434 | Perraud E, Wang J, Salomé M, Huneau JF, Lapidus N, Mariotti F. Plant and Animal Protein Intakes Largely Explain the Nutritional Quality and Health Value of Diets Higher in Plants: A Path Analysis in French Adults. 9. | Outcome
435 | Petersen JM, Naimi AI, Kirkpatrick SI, Bodnar LM. Equal Weighting of the Healthy Eating Index-2010 Components May not be Appropriate for Pregnancy. | Intervention/Exposure; Outcome
436 | Petersen KS, Murphy J, Whitbread J, Clifton PM, Keogh JB. The Effect of a Peanut-Enriched Weight Loss Diet Compared to a Low-Fat Weight Loss Diet on Body Weight, Blood Pressure, and Glycemic Control: A Randomized Controlled Trial. 14. | Intervention/Exposure
437 | Petroni, ML, Barbanti, FA, Bonadonna, R, Bruno, G, Caletti, MT, Croci, M, D’Eusebio, C, Dei Cas, A, Invitti, C, Merlo, F, Molteni, A, Pontiroli, A, Trento, M, Veronelli, A, Vigili de Kreutzenberg, S, Marchesini, G. Dysfunctional eating in type 2 diabetes mellitus: A multicenter Italian study of socio-demographic and clinical associations. Nutrition, Metabolism and Cardiovascular Diseases. 2019. 29:983-990. doi:10.1016/j.numecd.2019.06.006 | Study Design; Intervention/Exposure; Health Status; Outcome
438 | Petry, CliveJ, Ong, KenK, Hughes, IeuanA, Acerini, CarloL, Dunger, DavidB. Temporal Trends in Maternal Food Intake Frequencies and Associations with Gestational Diabetes: The Cambridge Baby Growth Study. Nutrients. 2019. 11:2822. doi:10.3390/nu11112822 | Intervention/Exposure
439 | Phillips, Quinn. REDUCED-CARBOHYDRATE, HIGH-PROTEIN DIET SHOWS BENEFITS IN TYPE 2. Diabetes Self-Management. 2021. 38:14-14. | Publication Status
440 | Pintó, X, Fanlo-Maresma, M, Corbella, E, et al. A Mediterranean Diet Rich in Extra-Virgin Olive Oil Is Associated with a Reduced Prevalence of Nonalcoholic Fatty Liver Disease in Older Individuals at High Cardiovascular Risk. Journal of Nutrition. 2019. 149:1920. | Intervention/Exposure; Comparator
441 | Piovesan CH, Gustavo A, Macagnan FE, Saboya PP, Oliveira MDS, Bodanese LC, Ludwig MWB, Closs VE, Feoli AMP. The Effect of Different Interventions for Lifestyle Modifications on the Number of Diagnostic Criteria and Clinical Aspects of Metabolic Syndrome. 19. | Intervention/Exposure
442 | Pletsch-Borba, L, Wernicke, C, Meyer, N, Huong Nguyen, T, Pohrt, A, Hornemann, S, Gerbracht, C, Pfeiffer, A, Spranger, J, Mai, K. A 36-month high-protein and high-unsaturated fatty-acid dietary intervention improves HbA1c in subjects aged 50-80y: preliminary results of the NutriAct Trial. Diabetologia. 2022. 65:S274-. doi:10.1007/s00125-022-05755-w | Publication Status
443 | Podboi ICR, Stephenson S, Pilic L, Graham CA, King A, Mavrommatis Y. Dietary Intake and TCF7L2 rs7903146 T Allele Are Associated with Elevated Blood Glucose Levels in Healthy Individuals. | Intervention/Exposure
444 | Pokharel P, Kyrø C, Olsen A, Tjønneland A, Murray K, Blekkenhorst LC, Bondonno CP, Hodgson JM, Bondonno NP. Vegetable, But Not Potato, Intake is Associated With a Lower Risk of Type 2 Diabetes in the Danish Diet, Cancer and Health Cohort. | Intervention/Exposure
445 | Popp CJ, Hu L, Kharmats AY, Curran M, Berube L, Wang C, Pompeii ML, Illiano P, St-Jules DE, Mottern M, Li H, Williams N, Schoenthaler A, Segal E, Godneva A, Thomas D, Bergman M, Schmidt AM, Sevick MA. Effect of a Personalized Diet to Reduce Postprandial Glycemic Response vs a Low-fat Diet on Weight Loss in Adults With Abnormal Glucose Metabolism and Obesity: A Randomized Clinical Trial. 5. | Intervention/Exposure; Outcome
446 | Porter Starr, KN, Connelly, MA, Orenduff, MC, McDonald, SR, Sloane, R, Huffman, KM, Kraus, WE, Bales, CW. Impact on cardiometabolic risk of a weight loss intervention with higher protein from lean red meat: Combined results of 2 randomized controlled trials in obese middle-aged and older adults. Journal of Clinical Lipidology. 2019. 13:920-931. doi:10.1016/j.jacl.2019.09.012 | Intervention/Exposure
447 | Prater MC, Scheurell AR, Paton CM, Cooper JA. Comparison of Blood Lipid Responses to Diets Enriched with Cottonseed Oil vs. Olive Oil in Adults with High Cholesterol in a Randomized Trial. | Study Duration
448 | Primo Martín, D, Izaola Jáuregui, O, López Gómez, JJ, Gómez Hoyos, E, Ortolá Buigues, A, Delgado, E, Díaz, G, Torres Torres, B, de Luis Román, DA. Effect of a Mediterranean-pattern diet on the metabolic response secondary to weight loss; role of the single nucleotide polymorphism (rs16147) of neuropeptide Y. Nutricion hospitalaria. 2020. 37:742-749. doi:10.20960/nh.02941 | Publication Language
449 | Primo, D, Izaola, O, Lopez, JJ, De Luis, DA. Brain derived neurotrophic factor (BDNF) polymorphism rs 10767664 affects metabolic parameters after weight loss secondary to high-fat hypocaloric diet with Mediterranean pattern. European Review for Medical and Pharmacological Sciences. 2021. 25:1944. | Intervention/Exposure; Comparator
450 | Qiao, Tian, Chen, Yue, Duan, Ruonan, Chen, Mengxue, Xue, Hongmei, Tian, Guo, Liang, Yi, Zhang, Jieyi, He, Fang, Yang, Dagang, Gong, Yunhui, Zhou, Rong, Cheng, Guo. Beyond protein intake: does dietary fat intake in the year preceding pregnancy and during pregnancy have an impact on gestational diabetes mellitus?. European Journal of Nutrition. 2021. 60:3461-3472. doi:10.1007/s00394-021-02525-z | Intervention/Exposure
451 | Quattrini, S, Pampaloni, B, Cianferotti, L, Fossi, C, Ottanelli, S, Gronchi, G, Duradoni, M, Di Tommaso, M, Dubini, V, Brandi, ML. Mediterranean diet adherence and dietary calcium intake in a group of pregnant women: Results of an Italian survey. Food Sci Nutr. 2021. 9:3426-3435. doi:10.1002/fsn3.2233 | Confounders
452 | Rabbani B, Chiti H, Sharifi F, Mazloomzadeh S. Effect of lifestyle modification for two years on obesity and metabolic syndrome components in elementary students: A community- based trial. 13. | Intervention/Exposure
453 | Raben, A, Vestentoft, PS, Brand-Miller, J, Jalo, E, Drummen, M, Simpson, L, Martinez, JA, Handjieva-Darlenska, T, Stratton, G, Huttunen-Lenz, M, Lam, T, Sundvall, J, Muirhead, R, Poppitt, S, Ritz, C, Pietiläinen, KH, Westerterp-Plantenga, M, Taylor, MA, Navas-Carretero, S, Handjiev, S, McNarry, MA, Hansen, S, Råman, L, Brodie, S, Silvestre, MP, Adam, TC, Macdonald, IA, San-Cristobal, R, Boyadjieva, N, Mackintosh, KA, Schlicht, W, Liu, A, Larsen, TM, Fogelholm, M. The PREVIEW intervention study: Results from a 3-year randomized 2 x 2 factorial multinational trial investigating the role of protein, glycaemic index and physical activity for prevention of type 2 diabetes. Diabetes, Obesity and Metabolism. 2021. 23:324-337. doi:10.1111/dom.14219 | Intervention/Exposure
454 | Rai SK, Gortmaker SL, Hu FB, Kanaya AM, Kandula NR, Sun Q, Bhupathiraju SN. A South Asian Mediterranean-style diet is associated with favorable adiposity measures and lower diabetes risk: The MASALA cohort. 31. | Size of Study Groups
455 | Ramesh G, Wood AC, Allison MA, Rich SS, Jensen ET, Chen YI, Rotter JI, Bertoni AG, Goodarzi MO. Associations between adherence to the dietary approaches to stop hypertension (DASH) diet and six glucose homeostasis traits in the Microbiome and Insulin Longitudinal Evaluation Study (MILES). | Study Design
456 | Ramezan, M, Asghari, G, Mirmiran, P, Tahmasebinejad, Z, Azizi, F. Mediterranean dietary patterns and risk of type 2 diabetes in the Islamic Republic of Iran. East Mediterr Health J. 2019. 25:896-904. doi:10.26719/emhj.19.035 | Size of Study Groups
457 | Ramírez-Manent JI, Altisench Jané B, Tomás Salvà M, Arroyo Bote S, González San Miguel HM, López-González ÁA. Influence of Educational Level and Healthy Habits on the Prevalence of Diabesity in a Spanish Working Population. 14. | Study Design; Intervention/Exposure
458 | Ramos-Levi A, Barabash A, Valerio J, García de la Torre N, Mendizabal L, Zulueta M, de Miguel MP, Diaz A, Duran A, Familiar C, Jimenez I, Del Valle L, Melero V, Moraga I, Herraiz MA, Torrejon MJ, Arregi M, Simón L, Rubio MA, Calle-Pascual AL. Genetic variants for prediction of gestational diabetes mellitus and modulation of susceptibility by a nutritional intervention based on a Mediterranean diet. 13. | Intervention/Exposure
459 | Rea, K, Jadallah, J, Nadpara, P, Goode, J-V“. Evaluation of the impact of a community-based, pharmacist-led weight loss program focused on a high-protein diet on risk factors for cardiovascular disease. Journal of the American Pharmacists Association. 2021. 61:S147. | Study Design; Intervention/Exposure
460 | Rebouillat P, Vidal R, Cravedi JP, Taupier-Letage B, Debrauwer L, Gamet-Payrastre L, Guillou H, Touvier M, Fezeu LK, Hercberg S, Lairon D, Baudry J, Kesse-Guyot E. Prospective association between dietary pesticide exposure profiles and type 2 diabetes risk in the NutriNet-Santé cohort. 21. | Intervention/Exposure
461 | Redman, LM, Drews, KL, Klein, S, Horn, LV, Wing, RR, Pi-Sunyer, X, Evans, M, Joshipura, K, Arteaga, SS, Cahill, AG, Clifton, RG, Couch, KA, Franks, PW, Gallagher, D, Haire-Joshu, D, Martin, CK, Peaceman, AM, Phelan, S, Thom, EA, Yanovski, SZ, Knowler, WC. Attenuated early pregnancy weight gain by prenatal lifestyle interventions does not prevent gestational diabetes in the LIFE-Moms consortium. Diabetes Research and Clinical Practice. 2021. 171. | Intervention/Exposure
462 | Reyes-López, MA, González-Leyva, CP, Rodríguez-Cano, AM, Rodríguez-Hernández, C, Colin-Ramírez, E, Estrada-Gutierrez, G, Muñoz-Manrique, CG, Perichart-Perera, O. Diet quality is associated with a high newborn size and reduction in the risk of low birth weight and small for gestational age in a group of mexican pregnant women: An observational study. Nutrients. 2021. 13. | Study Design
463 | Riddle, Judith. Plant-Based Eating and Diabetes. Today’s Dietitian. 2022. 24:6-6. | Publication Status
464 | Rinott, E, Youngster, I, Yaskolka Meir, A, Tsaban, G, Zelicha, H, Kaplan, A, Knights, D, Tuohy, K, Fava, F, Scholz, MU, Ziv, O, Reuven, E, Tirosh, A, Rudich, A, Bluher, M, Stumvoll, M, Ceglarek, U, Clement, K, Koren, O, Wang, DD, Hu, FB, Stampfer, MJ, Shai, I. Effects of Diet-Modulated Autologous Fecal Microbiota Transplantation on Weight Regain. Gastroenterology. 2021. 160:158-173 e10. doi:10.1053/j.gastro.2020.08.041 | Intervention/Exposure
465 | Riseberg, E, Lopez-Cepero, A, Mangano, KM, Tucker, KL, Mattei, J. Specific Dietary Protein Sources Are Associated with Cardiometabolic Risk Factors in the Boston Puerto Rican Health Study. Journal of the Academy of Nutrition and Dietetics. 2022. 122:298. | Intervention/Exposure
466 | Rodrigues, CÍNtiaCR, Riboldi, BÁRbaraP, Rodrigues, TicianaC, Sarmento, RobertaA, Antonio, JulianaP, Borba, RaquelA, Vieira, AdrieleP, Pasini, IsadoraS, De Almeida, JussaraC. 304-OR: Association of Eating Patterns and Diabetic Kidney Disease in Type 2 Diabetes. Diabetes. 2021. 70. doi:10.2337/db21-304-OR | Publication Status
467 | Röhling, M, Kempf, K, Banzer, W, Berg, A, Braumann, KM, Tan, S, Halle, M, McCarthy, D, Pinget, M, Predel, HG, Scholze, J, Toplak, H, Martin, S. Prediabetes conversion to normoglycemia is superior adding a low-carbohydrate and energy deficit formula diet to lifestyle intervention— a 12-month subanalysis of the acoorh trial. Nutrients. 2020. 12:1-13. doi:10.3390/nu12072022 | Intervention/Exposure
468 | Röhling, M, Martin, K, Ellinger, S, Schreiber, M, Martin, S, Kempf, K. Weight reduction by the low-insulin-method— a randomized controlled trial. Nutrients. 2020. 12:1-17. doi:10.3390/nu12103004 | Intervention/Exposure
469 | Rollo, ME, Baldwin, JN, Hutchesson, M, Aguiar, EJ, Wynne, K, Young, A, Callister, R, Haslam, R, Collins, CE. The Feasibility and Preliminary Efficacy of an eHealth Lifestyle Program in Women with Recent Gestational Diabetes Mellitus: A Pilot Study. Int J Environ Res Public Health. 2020. 17. doi:10.3390/ijerph17197115 | Intervention/Exposure; Comparator
470 | Roncero-Ramos, I, Alcala-Diaz, JF, Rangel-Zuniga, OA, Gomez-Delgado, F, Jimenez-Lucena, R, Garcia-Rios, A, Vals-Delgado, C, Romero-Baldonado, C, Luque, RM, Ordovas, JM, Perez-Martinez, P, Camargo, A, Lopez-Miranda, J. Prediabetes diagnosis criteria, type 2 diabetes risk and dietary modulation: The CORDIOPREV study. Clin Nutr. 2020. 39:492-500. doi:10.1016/j.clnu.2019.02.027 | Intervention/Exposure; Health Status
471 | Rosas, LG, Lv, N, Xiao, L, Lewis, MA, Venditti, EMJ, Zavella, P, Azar, K, Ma, J. Effect of a Culturally Adapted Behavioral Intervention for Latino Adults on Weight Loss Over 2 Years: A Randomized Clinical Trial. JAMA Netw Open. 2020. 3:e2027744. doi:10.1001/jamanetworkopen.2020.27744 | Intervention/Exposure
472 | Rosenberg, L, Robles, YP, Li, S, Ruiz-Narvaez, EA, Palmer, JR. A prospective study of yogurt and other dairy consumption in relation to incidence of type 2 diabetes among black women in the USA. Am J Clin Nutr. 2020. 112:512-518. doi:10.1093/ajcn/nqaa143 | Intervention/Exposure
473 | Rostgaard-Hansen AL, Lau CJ, Halkjær J, Olsen A, Toft U. An updated validation of the Dietary Quality Score: associations with risk factors for cardiometabolic diseases in a Danish population. | Study Design
474 | Ru Y, Wang N, Min Y, Wang X, McGurie V, Duan M, Xu X, Zhao X, Wu YH, Lu Y, Hsing AW, Zhu S. Characterization of dietary patterns and assessment of their relationships with metabolomic profiles: A community-based study. 40. | Study Design
475 | Rydhög, B, Granfeldt, Y, Frassetto, L, Fontes-Villalba, M, Carrera-Bastos, P, Jönsson, T. Assessing compliance with Paleolithic diet by calculating Paleolithic Diet Fraction as the fraction of intake from Paleolithic food groups. Clinical Nutrition Experimental. 2019. 25:29-35. doi:10.1016/j.yclnex.2019.03.002 | Health Status
476 | Sadeghian, M, Hosseini, SA, Zare Javid, A, Ahmadi Angali, K, Mashkournia, A. Effect of Fasting-Mimicking Diet or Continuous Energy Restriction on Weight Loss, Body Composition, and Appetite-Regulating Hormones Among Metabolically Healthy Women with Obesity: a Randomized Controlled, Parallel Trial. Obes Surg. 2021. 31:2030-2039. doi:10.1007/s11695-020-05202-y | Intervention/Exposure; Study Duration
477 | Sadiya A, Jakapure V, Shaar G, Adnan R, Tesfa Y. Lifestyle intervention in early pregnancy can prevent gestational diabetes in high-risk pregnant women in the UAE: a randomized controlled trial. 22. | Intervention/Exposure; Comparator
478 | Said, MS, El Sayed, IT, Ibrahim, EE, Khafagy, GM. Effect of DASH Diet Versus Healthy Dietary Advice on the Estimated Atherosclerotic Cardiovascular Disease Risk. J Prim Care Community Health. 2021. 12:2150132720980952. doi:10.1177/2150132720980952 | Intervention/Exposure; Comparator
479 | Saidj, S, Ruchat, SM, Henderson, M, Drapeau, V, Mathieu, ME. Which healthy lifestyle habits mitigate the risk of obesity and cardiometabolic risk factors in Caucasian children exposed to in utero adverse gestational factors?. Nutr Metab Cardiovasc Dis. 2021. 31:286-296. doi:10.1016/j.numecd.2020.08.008 | Intervention/Exposure; Outcome
480 | Sakurai M, Ishizaki M, Morikawa Y, Kido T, Naruse Y, Nakashima Y, Okamoto C, Nogawa K, Watanabe Y, Suwazono Y, Hozawa A, Yoshita K, Nakagawa H. Frequency of consumption of balanced meals, bodyweight gain and incident risk of glucose intolerance in Japanese men and women: A cohort study. 12. | Intervention/Exposure
481 | Salas-Salvadó, J, Díaz-López, A, Ruiz-Canela, M, Basora, J, Fitó, M, Corella, D, Serra-Majem, L, Wärnberg, J, Romaguera, D, Estruch, R, Vidal, J, Alfredo Martínez, J, Arós, F, Vázquez, C, Ros, E, Vioque, J, López-Miranda, J, Bueno-Cavanillas, A, Tur, JA, Tinahones, FJ, Martín, V, Lapetra, J, Pintó, X, Daimiel, L, Delgado-Rodríguez, M, Matía, P, Gómez-Gracia, E, Díez-Espino, J, Babio, N, Castañer, O, Sorlí, JV, Fiol, M, Zulet, Á M, Bulló, M, Goday, A, Martínez-González, Á M. Effect of a lifestyle intervention program with energy-restricted Mediterranean diet and exercise on weight loss and cardiovascular risk factors: One-year results of the PREDIMED-Plus trial. Diabetes Care. 2019. 42:777-788. doi:10.2337/dc18-0836 | Intervention/Exposure; Comparator
482 | Sandborg, J, Soderstrom, E, Henriksson, P, Bendtsen, M, Henstrom, M, Leppanen, MH, Maddison, R, Migueles, JH, Blomberg, M, Lof, M. Effectiveness of a Smartphone App to Promote Healthy Weight Gain, Diet, and Physical Activity During Pregnancy (HealthyMoms): Randomized Controlled Trial. JMIR Mhealth Uhealth. 2021. 9:e26091. doi:10.2196/26091 | Intervention/Exposure; Outcome
483 | Santos KD, Rosado EL, da Fonseca ACP, Belfort GP, da Silva LBG, Ribeiro-Alves M, Zembrzuski VM, Martínez JA, Saunders C. FTO and ADRB2 Genetic Polymorphisms Are Risk Factors for Earlier Excessive Gestational Weight Gain in Pregnant Women with Pregestational Diabetes Mellitus: Results of a Randomized Nutrigenetic Trial. 14. | Health Status
484 | Santos, ASAC, Rodrigues, APS, Rosa, LPS, Noll, M, Silveira, EA. Traditional Brazilian diet and olive oil reduce cardiometabolic risk factors in severely obese individuals: A randomized trial. Nutrients. 2020. 12. doi:10.3390/nu12051413 | Intervention/Exposure
485 | Šarac, Jelena, Havaš Auguštin, Dubravka, Lovrić, Mario, Stryeck, Sarah, Šunić, Iva, Novokmet, Natalija, Missoni, Saša. A Generation Shift in Mediterranean Diet Adherence and Its Association with Biological Markers and Health in Dalmatia, Croatia. Nutrients. 2021. 13:4564-4564. doi:10.3390/nu13124564 | Study Design
486 | Saslow LR, Jones LM, Sen A, Wolfson JA, Diez HL, O’Brien A, Leung CW, Bayandorian H, Daubenmier J, Missel AL, Richardson C. Comparing Very Low-Carbohydrate vs DASH Diets for Overweight or Obese Adults With Hypertension and Prediabetes or Type 2 Diabetes: A Randomized Trial. 21. | Intervention/Exposure; Size of Study Groups
487 | Sayón-Orea, C, Razquin, C, Bulló, M, Corella, D, Fitó, M, Romaguera, D, Vioque, J, Alonso-Gómez, ÁM, Wärnberg, J, Martínez, JA, etal, . Effect of a Nutritional and Behavioral Intervention on Energy-Reduced Mediterranean Diet Adherence Among Patients With Metabolic Syndrome: interim Analysis of the PREDIMED-Plus Randomized Clinical Trial. JAMA. 2019. 322:1486-1499. doi:10.1001/jama.2019.14630 | Intervention/Exposure; Outcome
488 | Schembre, SM, Jospe, MR, Giles, ED, Sears, DD, Liao, Y, Basen-Engquist, KM, Thomson, CA. A low-glucose eating pattern improves biomarkers of postmenopausal breast cancer risk: An exploratory secondary analysis of a randomized feasibility trial. Nutrients. 2021. 13. | Intervention/Exposure; Outcome
489 | Schmidt, KelseyA, Cromer, Gail, Burhans, MaggieS, Kuzma, JessicaN, Hagman, DerekK, Fernando, Imashi, Murray, Merideth, Utzschneider, KristinaM, Holte, Sarah, Kraft, Jana, Kratz, Mario. The impact of diets rich in low-fat or full-fat dairy on glucose tolerance and its determinants: a randomized controlled trial. American Journal of Clinical Nutrition. 2021. 113:534-547. doi:10.1093/ajcn/nqaa301 | Intervention/Exposure
490 | Schnermann, ME, Schulz, C-A, Herder, C, Alexy, U, Nöthlings, U. A lifestyle pattern during adolescence is associated with cardiovascular risk markers in young adults: Results from the DONALD cohort study. Journal of Nutritional Science. 2021. 10. | Intervention/Exposure; Comparator
491 | Schroder, H, Zomeno, MD, Martinez-Gonzalez, MA, Salas-Salvado, J, Corella, D, Vioque, J, Romaguera, D, Martinez, JA, Tinahones, FJ, Miranda, JL, Estruch, R, Bueno-Cavanillas, A, Alonso Gomez, AM, Tur, JA, Warnberg, J, Serra-Majem, L, Martin, V, Vazquez, C, Lapetra, J, Pinto, X, Vidal, J, Daimiel, L, Gaforio, JJ, Matia-Martin, P, Ros, E, Lassale, C, Ruiz-Canela, M, Babio, N, Sorli, JV, Garcia-Arellano, A, Diaz-Lopez, A, Fito, M, Castaner, O, REDIMED-Plus investigators P. Validity of the energy-restricted Mediterranean Diet Adherence Screener. Clin Nutr. 2021. 40:4971-4979. doi:10.1016/j.clnu.2021.06.030 | Outcome
492 | Schutte, Sophie, Esser, Diederik, Siebelink, Els, Michielsen, CharlotteJR, Daanje, Monique, Matualatupauw, JuriC, Boshuizen, HendriekC, Mensink, Marco, Afman, LydiaA, team, The Wageningen Belly Fat Study. Diverging metabolic effects of 2 energy-restricted diets differing in nutrient quality: a 12-week randomized controlled trial in subjects with abdominal obesity. American Journal of Clinical Nutrition. 2022. 116:132-150. doi:10.1093/ajcn/nqac025 | Intervention/Exposure
493 | Scott, E, Shehata, M, Panesar, A, Summers, C, Dale, J. The Low Carb Program for people with type 2 diabetes and pre-diabetes: a mixed methods feasibility study of signposting from general practice. BJGP Open. 2022. 6:1. | Study Design; Intervention/Exposure
494 | Seah, JowyYH, Koh, Woon-Puay, Yuan, Jian-Min, van Dam, RobM. Rice intake and risk of type 2 diabetes: the Singapore Chinese Health Study. European Journal of Nutrition. 2019. 58:3349-3360. doi:10.1007/s00394-018-1879-7 | Intervention/Exposure
495 | Seguin, R, Folta, S, Marshall, G, Graham, M, Strogatz, DS. The effect of a community-based healthy lifestyle behavior change program on simple 7 score among rural women. Circulation. 2019. 139. doi:10.1161/circ.139.suppl_1.P144 | Intervention/Exposure; Publication Status
496 | Seguin-Fowler, RA, Strogatz, D, Graham, ML, Eldridge, GD, Marshall, GA, Folta, SC, Pullyblank, K, Nelson, ME, Paul, L. The Strong Hearts, Healthy Communities Program 2.0: An RCT Examining Effects on Simple 7. Am J Prev Med. 2020. 59:32-40. doi:10.1016/j.amepre.2020.01.027 | Intervention/Exposure; Outcome
497 | Seixas MB, Pereira DAG, Ghisi GLM, Batalha APDB, Santos CVO, Ponciano IC, Oh P, Silva LPD. Exercise and Lifestyle Education program for Brazilians living with prediabetes and diabetes: A pilot randomized trial. 16. | Intervention/Exposure
498 | Seral-Cortes, M, Sabroso-Lasa, S, De Miguel-Etayo, P, Gonzalez-Gross, M, Gesteiro, E, Molina-Hidalgo, C, De Henauw, S, Erhardt, E, Censi, L, Manios, Y, Karaglani, E, Widhalm, K, Kafatos, A, Beghin, L, Meirhaeghe, A, Salazar-Tortosa, D, Ruiz, JR, Moreno, LA, Esteban, LM, Labayen, I. Interaction Effect of the Mediterranean Diet and an Obesity Genetic Risk Score on Adiposity and Metabolic Syndrome in Adolescents: The HELENA Study. Nutrients. 2020. 12. doi:10.3390/nu12123841 | Study Design
499 | Seremet Kurklu, N, Karatas Torun, N, Ozen Kucukcetin, I, Akyol, A. Is there a relationship between the dietary inflammatory index and metabolic syndrome among adolescents?. J Pediatr Endocrinol Metab. 2020. 33:495-502. doi:10.1515/jpem-2019-0409 | Study Design; Intervention/Exposure
500 | Shahinfar, H, Amini, MR, Payandeh, N, Naghshi, S, Sheikhhossein, F, Djafarian, K, Shab-Bidar, S. The link between plant-based diet indices with biochemical markers of bone turn over, inflammation, and insulin in Iranian older adults. Food Sci Nutr. 2021. 9:3000-3014. doi:10.1002/fsn3.2258 | Study Design
501 | Shakeri, Z, Mirmiran, P, Khalili-Moghadam, S, Hosseini-Esfahani, F, Ataie-Jafari, A, Azizi, F. Empirical dietary inflammatory pattern and risk of metabolic syndrome and its components: Tehran Lipid and Glucose Study. Diabetology and Metabolic Syndrome. 2019. 11. doi:10.1186/s13098-0190411-4 | Outcome
502 | Shang X, Li Y, Xu H, Zhang Q, Liu A, Du S, Guo H, Ma G. Leading dietary determinants identified using machine learning techniques and a healthy diet score for changes in cardiometabolic risk factors in children: a longitudinal analysis. 19. | Country
503 | Shang, X, Li, Y, Xu, H, Zhang, Q, Hu, X, Liu, A, Du, S, Li, T, Guo, H, Li, Y, etal, . Effect of multidimensional lifestyle interventions on metabolic risk reduction in children: a cluster randomised controlled trial. Preventive medicine. 2020. 133. doi:10.1016/j.ypmed.2020.106010 | Intervention/Exposure
504 | Shang, X, Li, Y, Xu, H, Zhang, Q, Liu, A, Du, S, Ma, G. Meal patterns and changes in cardiometabolic risk factors in children: a longitudinal analysis. Nutrients. 2020. 12. doi:10.3390/nu12030799 | Intervention/Exposure
505 | Shang, X, Li, Y, Xu, H, Zhang, Q, Liu, A, Ma, G. The Clustering of Low Diet Quality, Low Physical Fitness, and Unhealthy Sleep Pattern and Its Association with Changes in Cardiometabolic Risk Factors in Children. Nutrients. 2020. 12. doi:10.3390/nu12020591 | Intervention/Exposure; Country
506 | Shemirani, F, Djafarian, K, Fotouhi, A, Azadbakht, L, Rezaei, N, Chamari, M, Shabani, S, Mahmoudi, M. Effect of Paleolithic-based low-carbohydrate vs. moderate-carbohydrate diets with portion-control and calorie-counting on CTRP6, asprosin and metabolic markers in adults with metabolic syndrome: A randomized clinical trial. Clinical Nutrition ESPEN. 2022. 48:87. | Study Duration
507 | Shen QM, Li HL, Li ZY, Jiang YF, Ji XW, Tan YT, Xiang YB. Joint impact of BMI, physical activity and diet on type 2 diabetes: findings from two population-based cohorts in China. | Country
508 | Shen XM, Huang YQ, Zhang XY, Tong XQ, Zheng PF, Shu L. Association between dietary patterns and prediabetes risk in a middle-aged Chinese population. 19. | Study Design
509 | Shen XM, Shu L, Huang YQ, Zhang XY, Zheng PF, Zhu Q. Association between dietary patterns and glycemic control in a middle-aged Chinese population. | Study Design
510 | Shen, Xiao-Ming, Shu, Long, Huang, Yi-Qian, Zhang, Xiao-Yan, Zheng, Pei-Fen, Zhu, Qin. Association between dietary patterns and glycaemic control in a middle-aged Chinese population. Public Health Nutrition. 2022. 25:2197-2205. doi:10.1017/S1368980021003931 | Study Design
511 | Shi J, Fang H, Guo Q, Yu D, Ju L, Cheng X, Piao W, Xu X, Li Z, Mu D, Zhao L, He L. Association of Dietary Patterns with Metabolic Syndrome in Chinese Children and Adolescents Aged 7-17: The China National Nutrition and Health Surveillance of Children and Lactating Mothers in 2016-2017. 14. | Study Design
512 | Shin J, Zhou X, Tan JTM, Hyppönen E, Benyamin B, Lee SH. Lifestyle Modifies the Diabetes-Related Metabolic Risk, Conditional on Individual Genetic Differences. 13. | Intervention/Exposure
513 | Shin, D, Lee, KW. Dietary carbohydrates interacts with AMY1 polymorphisms to influence the incidence of type 2 diabetes in Korean adults. Scientific reports. 2021. 11:16788. | Intervention/Exposure
514 | Shin, Y, Kim, Y. Psychological Stress Accompanied by a Low-Variety Diet Is Positively Associated with Type 2 Diabetes in Middle-Aged Adults. Nutrients. 2020. 12. doi:10.3390/nu12092612 | Study Design; Intervention/Exposure
515 | Shivappa, N, Hebert, JR, Akhoundan, M, Mirmiran, P, Rashidkhani, B. Association between inflammatory potential of diet and odds of gestational diabetes mellitus among Iranian women. J Matern Fetal Neonatal Med. 2019. 32:3552-3558. doi:10.1080/14767058.2018.1466275 | Study Design
516 | Singer, J, Putulik Kidlapik, C, Martin, B, Dean, HJ, Trepman, E, Embil, JM. Food consumption, obesity and abnormal glycaemic control in a Canadian Inuit community. Clinical Obesity. 2014. 4:316. | Study Design
517 | Siregar, DAS, Rianda, D, Irwinda, R, Dwi Utami, A, Hanifa, H, Shankar, AH, Agustina, R. Associations between diet quality, blood pressure, and glucose levels among pregnant women in the Asian megacity of Jakarta. PLoS One. 2020. 15:e0242150. doi:10.1371/journal.pone.0242150 | Study Design
518 | Skelly, LE, Barbour-Tuck, EN, Kurgan, N, Calleja, M, Klentrou, P, Falk, B, Josse, AR. Neutral Effect of Increased Dairy Product Intake, as Part of a Lifestyle Modification Program, on Cardiometabolic Health in Adolescent Girls With Overweight/Obesity: A Secondary Analysis From a Randomized Controlled Trial. Front Nutr. 2021. 8:673589. doi:10.3389/fnut.2021.673589 | Intervention/Exposure
519 | Skurk T, Bosy-Westphal A, Grünerbel A, Kabisch S, Keuthage W, Kronsbein P, Müssig K, Pfeiffer AFH, Simon MC, Tombek A, Weber KS, Rubin D. Dietary recommendations for persons with type 2 diabetes mellitus. | Study Design; Health Status; Publication Status
520 | Slomski A. Low-Carbohydrate, High-Fat Diet Improved Type 2 Diabetes Without Restricting Calories. 329. | Publication Status
521 | Sluijs, I, Van Der Schouw, YT, Van Der A, DL, Spijkerman, AM, Hu, FB, Grobbee, DE, Beulens, JW. Carbohydrate quantity and quality and risk of type 2 diabetes in the European Prospective Investigation into Cancer and Nutrition-Netherlands (EPIC-NL) study. American Journal of Clinical Nutrition. 2010. 92:905. | Intervention/Exposure
522 | Smith, PJ, Mabe, SM, Sherwood, A, Doraiswamy, PM, Welsh-Bohmer, KA, Burke, JR, Kraus, WE, Lin, PH, Browndyke, JN, Babyak, MA, Hinderliter, AL, Blumenthal, JA. Metabolic and Neurocognitive Changes Following Lifestyle Modification: Examination of Biomarkers from the ENLIGHTEN Randomized Clinical Trial. J Alzheimers Dis. 2020. 77:1793-1803. doi:10.3233/JAD-200374 | Intervention/Exposure
523 | Sobiecki JG, Imamura F, Davis CR, Sharp SJ, Koulman A, Hodgson JM, Guevara M, Schulze MB, Zheng JS, Agnoli C, Bonet C, Colorado-Yohar SM, Fagherazzi G, Franks PW, Gundersen TE, Jannasch F, Kaaks R, Katzke V, Molina-Montes E, Nilsson PM, Palli D, Panico S, Papier K, Rolandsson O, Sacerdote C, Tjønneland A, Tong TYN, van der Schouw YT, Danesh J, Butterworth AS, Riboli E, Murphy KJ, Wareham NJ, Forouhi NG. A nutritional biomarker score of the Mediterranean diet and incident type 2 diabetes: Integrated analysis of data from the MedLey randomised controlled trial and the EPIC-InterAct case-cohort study. 20. | Intervention/Exposure; Outcome
524 | Soldevila-Domenech N, Pastor A, Sala-Vila A, Lázaro I, Boronat A, Muñoz D, Castañer O, Fagundo B, Corella D, Fernández-Aranda F, Martínez-González MÁ, Salas-Salvadó J, Fitó M, de la Torre R. Sex differences in endocannabinoids during 3 years of Mediterranean diet intervention: Association with insulin resistance and weight loss in a population with metabolic syndrome. 9. | Intervention/Exposure
525 | Soltani S, Aminianfar A, Hajianfar H, Azadbakht L, Shahshahan Z, Esmaillzadeh A. Association between dietary inflammatory potential and risk of developing gestational diabetes: a prospective cohort study. 20. | Intervention/Exposure
526 | Song, YM, Lee, K. Genetic and environmental associations between insulin resistance and weight-related traits and future weight change. Nutrition. 2020. 79-80:110939. doi:10.1016/j.nut.2020.110939 | Intervention/Exposure
527 | Soria-Contreras, DC, Rifas-Shiman, SL, Aris, IM, Perng, W, Switkowski, KM, Tellez-Rojo, MM, Trejo-Valdivia, B, Lopez-Ridaura, R, Oken, E. Weight Trajectories After Delivery are Associated with Adiposity and Cardiometabolic Markers at 3 Years Postpartum Among Women in Project Viva. J Nutr. 2020. 150:1889-1898. doi:10.1093/jn/nxaa104 | Intervention/Exposure
528 | Sotos-Prieto M, Ortolá R, Ruiz-Canela M, Garcia-Esquinas E, Martínez-Gómez D, Lopez-Garcia E, Martínez-González MÁ, Rodriguez-Artalejo F. Association between the Mediterranean lifestyle, metabolic syndrome and mortality: a whole-country cohort in Spain. 20. | Intervention/Exposure; Comparator
529 | Steele, CC, Steele, TJ, Gwinner, M, Rosenkranz, SK, Kirkpatrick, K. The relationship between dietary fat intake, impulsive choice, and metabolic health. Appetite. 2021. 165. doi:10.1016/j.appet.2021.105292 | Intervention/Exposure; Study Duration
530 | Stentz, FB, Mikhael, A, Kineish, O, Christman, J, Sands, C. High protein diet leads to prediabetes remission and positive changes in incretins and cardiovascular risk factors. Nutrition, Metabolism and Cardiovascular Diseases. 2021. 31:1227-1237. doi:10.1016/j.numecd.2020.11.027 | Intervention/Exposure
531 | Storz, MA. Reduced Diabetes Medication Needs With a Plant-Based Diet. J Am Coll Nutr. 2020. 39:574-577. doi:10.1080/07315724.2019.1698381 | Study Design; Publication Status
532 | Strączek, K, Horodnicka-Józwa, A, Szmit-Domagalska, J, Jackowski, T, Safranow, K, Petriczko, E, Walczak, M. Familial dietary intervention in children with excess body weight and its impact on eating habits, anthropometric and biochemical parameters. Frontiers in Endocrinology. 2022. 13. | Intervention/Exposure
533 | Stratakis N, Siskos AP, Papadopoulou E, Nguyen AN, Zhao Y, Margetaki K, Lau CE, Coen M, Maitre L, Fernández-Barrés S, Agier L, Andrusaityte S, Basagaña X, Brantsaeter AL, Casas M, Fossati S, Grazuleviciene R, Heude B, McEachan RR, Meltzer HM, Millett C, Rauber F, Robinson O, Roumeliotaki T, Borras E, Sabidó E, Urquiza J, Vafeiadi M, Vineis P, Voortman T, Wright J, Conti DV, Vrijheid M, Keun HC, Chatzi L. Urinary metabolic biomarkers of diet quality in European children are associated with metabolic health. 11. | Study Design; Outcome
534 | Sugihiro, T, Yoneda, M, Ohno, H, Oki, K, Hattori, N. Associations of nutrient intakes with obesity and diabetes mellitus in the longitudinal medical surveys of Japanese Americans. Journal of Diabetes Investigation. 2019. 10:1229-1236. doi:10.1111/jdi.13010 | Intervention/Exposure
535 | Suliga, Edyta, Brola, Waldemar, Sobaś, Kamila, Cieśla, Elżbieta, Jasińska, Elżbieta, Gołuch, Katarzyna, Głuszek, Stanisław. Dietary Patterns and Metabolic Disorders in Polish Adults with Multiple Sclerosis. Nutrients. 2022. 14:1927-1927. doi:10.3390/nu14091927 | Study Design; Health Status
536 | Sun Y, Chen S, Zhao X, Wang Y, Lan Y, Jiang X, Gao X, Wu S, Wang L. Adherence to the Dietary Approaches to Stop Hypertension diet and non-alcoholic fatty liver disease. | Study Design; Country
537 | Sun, J, Ruan, Y, Xu, N, Wu, P, Lin, N, Yuan, K, An, S, Kang, P, Li, S, Huang, Q, Yingzhang, , Li, Y, Su, J, Ma, W, Chen, B, Zhang, X, Chen, X, Liang, Y, Lu, Z, Deng, G, Zhang, Z, Wang, Y, Wen, W, Zhang, H, Chen, H. The effect of dietary carbohydrate and calorie restriction on weight and metabolic health in overweight/obese individuals: a multi-center randomized controlled trial. BMC Medicine. 2023. 21. | Intervention/Exposure
538 | Taheri E, Bostick RM, Hatami B, Pourhoseingholi MA, Asadzadeh Aghdaei H, Moslem A, Mousavi Jarrahi A, Zali MR. Dietary and Lifestyle Inflammation Scores Are Inversely Associated with Metabolic-Associated Fatty Liver Disease among Iranian Adults: A Nested Case-Control Study. 152. | Outcome
539 | Tang, N, Wu, Y, Chen, Y, Chen, Q, Wu, W, Jing, J, Cai, L. Association between postpartum low-carbohydrate-diet scores and glucose levels in Chinese women. Nutrition. 2021. 89:111305. doi:10.1016/j.nut.2021.111305 | Intervention/Exposure
540 | Tanner, H, Barrett, HL, Callaway, LK, Wilkinson, SA, Nitert, MD. Consumption of a low carbohydrate diet in overweight or obese pregnant women is associated with longer gestation of pregnancy. Nutrients. 2021. 13. | Intervention/Exposure
541 | Taylor R, Rollo ME, Baldwin JN, Hutchesson M, Aguiar EJ, Wynne K, Young A, Callister R, Collins CE. Evaluation of a Type 2 diabetes risk reduction online program for women with recent gestational diabetes: a randomised trial. 19. | Intervention/Exposure; Comparator
542 | Terschüren C, Damerau L, Petersen EL, Harth V, Augustin M, Zyriax BC. Association of Dietary Pattern, Lifestyle and Chronotype with Metabolic Syndrome in Elderly-Lessons from the Population-Based Hamburg City Health Study. 19. | Study Design; Outcome
543 | Tettamanzi, F, Bagnardi, V, Louca, P, Nogal, A, Monti, GS, Mambrini, SP, Lucchetti, E, Maestrini, S, Mazza, S, Rodriguez-Mateos, A, Scacchi, M, Valdes, AM, Invitti, C, Menni, C. A high protein diet is more effective in improving insulin resistance and glycemic variability compared to a mediterranean diet—a cross-over controlled inpatient dietary study. Nutrients. 2021. 13. | Study Duration
544 | Teymoori F, Mokhtari E, Farhadnejad H, Mirmiran P, Rad HA, Azizi F. The dietary and lifestyle indices of insulin resistance are associated with increased risk of cardiovascular diseases: A prospective study among an Iranian adult population. | Intervention/Exposure; Outcome
545 | Teymoori, F, Mokhtari, E, Salehi, P, Hosseini-Esfahani, F, Mirmiran, P, Azizi, F. A nutrient pattern characterized by vitamin A, C, B6, potassium, and fructose is associated with reduced risk of insulin-related disorders: A prospective study among participants of Tehran lipid and glucose study. Diabetol Metab Syndr. 2021. 13:12. doi:10.1186/s13098-021-00629-4 | Intervention/Exposure
546 | Thao, U, Lajous, M, Laouali, N, Severi, G, Boutron-Ruault, M-C, MacDonald, CJ. Replacing processed red meat with alternative protein sources is associated with a reduced risk of hypertension and diabetes in a prospective cohort of French women. The British journal of nutrition. 2022. 1. | Intervention/Exposure; Comparator
547 | Thomas MS, Puglisi M, Malysheva O, Caudill MA, Sholola M, Cooperstone JL, Fernandez ML. Eggs Improve Plasma Biomarkers in Patients with Metabolic Syndrome Following a Plant-Based Diet-A Randomized Crossover Study. 14. | Intervention/Exposure; Study Duration
548 | Titcomb TJ, Liu B, Wahls TL, Snetselaar LG, Shadyab AH, Tabung FK, Saquib N, Arcan C, Tinker LF, Wallace RB, Bao W. Comparison of the ketogenic ratio of macronutrients with the low-carbohydrate diet score and their association with risk of type 2 diabetes in postmenopausal women: A secondary analysis of the women’s health initiative. | Intervention/Exposure
549 | Tomaino, L, Reyes Suarez, D, Reyes Dominguez, A, Garcia Cruz, LM, Ramos Diaz, M, Serra Majem, L. Adherence to Mediterranean diet is not associated with birthweight - Results form a sample of Canarian pregnant women. Nutr Hosp. 2020. 37:86-92. doi:10.20960/nh.02780 | Study Design; Outcome
550 | Tosi M, Matelloni IA, Mancini M, Andreassi A, Scopari A, Rossi A, Verduci E, Berra C, Manfrini R, Banderali G, Pecori Giraldi F, Folli F. Multiple beneficial effects of 1-year nutritional-behavioral intervention on anthropometric and metabolic parameters in overweight and obese boys. | Study Design; Intervention/Exposure
551 | Tresserra-Rimbau A, Castro-Barquero S, Becerra-Tomás N, Babio N, Martínez-González MÁ, Corella D, Fitó M, Romaguera D, Vioque J, Alonso-Gomez AM, Wärnberg J, Martínez JA, Serra-Majem L, Estruch R, Tinahones FJ, Lapetra J, Pintó X, Tur JA, López-Miranda J, Cano-Ibáñez N, Delgado-Rodríguez M, Matía-Martín P, Daimiel L, Martín Sánchez V, Vidal J, Vázquez C, Ros E, Basterra FJ, Fernández de la Puente M, Asensio EM, Castañer O, Bullón-Vela V, Tojal-Sierra L, Gómez-Gracia E, Cases-Pérez E, Konieczna J, García-Ríos A, Casañas-Quintana T, Bernal-Lopez MR, Santos-Lozano JM, Esteve-Luque V, Bouzas C, Vázquez-Ruiz Z, Palau-Galindo A, Barragan R, López Grau M, Razquín C, Goicolea-Güemez L, Toledo E, Vergaz MV, Lamuela-Raventós RM, Salas-Salvadó J. Adopting a High-Polyphenolic Diet Is Associated with an Improved Glucose Profile: Prospective Analysis within the PREDIMED-Plus Trial. 11. | Intervention/Exposure
552 | Trimigno, A, Khakimov, B, Savorani, F, Poulsen, SK, Astrup, A, Dragsted, LO, Engelsen, SB. Human urine (1)H NMR metabolomics reveals alterations of protein and carbohydrate metabolism when comparing habitual Average Danish diet vs. healthy New Nordic diet. Nutrition. 2020. 79-80:110867. doi:10.1016/j.nut.2020.110867 | Outcome
553 | Trouwborst, I, Gijbels, A, Jardon, KM, Siebelink, E, Hul, GB, Wanders, L, Erdos, B, Péter, S, Singh-Povel, CM, de Vogel-van den Bosch, J, Adriaens, ME, Arts, ICW, Thijssen, DHJ, Feskens, EJM, Goossens, GH, Afman, LA, Blaak, EE. Cardiometabolic health improvements upon dietary intervention are driven by tissue-specific insulin resistance phenotype: A precision nutrition trial. Cell Metabolism. 2023. 35:71. | Intervention/Exposure
554 | Tryggvadottir, EA, Halldorsson, TI, Landberg, R, Hrolfsdottir, L, Birgisdottir, BE, Magnusdottir, OK, Hreidarsdottir, IT, Hardardottir, H, Gunnarsdottir, I. Higher Alkylresorcinol Concentrations, a Consequence of Whole-Grain Intake, are Inversely Associated with Gestational Diabetes Mellitus in Iceland. The Journal of nutrition. 2021. 151:1159. | Intervention/Exposure
555 | Tryggvadottir, EA, Gunnarsdottir, I, Birgisdottir, BE, Hrolfsdottir, L, Landberg, R, Hreidarsdottir, IT, Hardardottir, H, Halldorsson, TI. Early pregnancy plasma fatty acid profiles of women later diagnosed with gestational diabetes. BMJ Open Diabetes Res Care. 2021. 9. doi:10.1136/bmjdrc-2021-002326 | Intervention/Exposure
556 | Tsaban, G, Yaskolka Meir, A, Rinott, E, Zelicha, H, Kaplan, A, Shalev, A, Katz, A, Rudich, A, Tirosh, A, Shelef, I, Youngster, I, Lebovitz, S, Israeli, N, Shabat, M, Brikner, D, Pupkin, E, Stumvoll, M, Thiery, J, Ceglarek, U, Heiker, JT, Korner, A, Landgraf, K, von Bergen, M, Bluher, M, Stampfer, MJ, Shai, I. The effect of green Mediterranean diet on cardiometabolic risk; a randomised controlled trial. Heart. 2020. doi:10.1136/heartjnl-2020-317802 | Intervention/Exposure; Comparator
557 | Tsai TJ, Li MC. Adherence to the Taiwan Daily Food Guide and the Risk of Type 2 Diabetes: A Populational Study in Taiwan. 20. | Study Design
558 | Tunçer, E, Keser, A, Ünsal, EN, Güneş, SO, Akın, O. The Correlation Between Adherence to Mediterranean Diet and HOMA-IR in Children and Adolescents. Çocuk ve Adölesanlarda Akdeniz Diyetine Uyum ile HOMA-IR Arasındaki İlişki. 2022. 20:188. | Study Design
559 | Tuomainen, M, Karkkainen, O, Leppanen, J, Auriola, S, Lehtonen, M, Savolainen, MJ, Hermansen, K, Riserus, U, Akesson, B, Thorsdottir, I, Kolehmainen, M, Uusitupa, M, Poutanen, K, Schwab, U, Hanhineva, K. Quantitative assessment of betainized compounds and associations with dietary and metabolic biomarkers in the randomized study of the healthy Nordic diet (SYSDIET). Am J Clin Nutr. 2019. 110:1108-1118. doi:10.1093/ajcn/nqz179 | Intervention/Exposure; Comparator
560 | Turner-McGrievy GM, Wilson MJ, Carswell J, Okpara N, Aydin H, Bailey S, Davey M, Hutto B, Wilcox S, Friedman DB, Sarzynski MA, Liese AD. A 12-Week Randomized Intervention Comparing the Healthy US, Mediterranean, and Vegetarian Dietary Patterns of the US Dietary Guidelines for Changes in Body Weight, Hemoglobin A1c, Blood Pressure, and Dietary Quality among African American Adults. 153. | Intervention/Exposure
561 | Tzenios, N, Lewis, ED, Crowley, DC, Chahine, M, Evans, M. Examining the Efficacy of a Very-Low-Carbohydrate Ketogenic Diet on Cardiovascular Health in Adults with Mildly Elevated Low-Density Lipoprotein Cholesterol in an Open-Label Pilot Study. Metabolic Syndrome and Related Disorders. 2022. 20:94. | Study Design; Intervention/Exposure
562 | Uçar, Z, Akman, M. Mediterranean type diet protects adult individuals from diabetes. Progress in Nutrition. 2021. 23. | Study Design
563 | Unwin, D, Delon, C, Unwin, J, Tobin, S, Taylor, R. What predicts drug-free type 2 diabetes remission? Insights from an 8-year general practice service evaluation of a lower carbohydrate diet with weight loss. BMJ Nutrition, Prevention and Health. 2023. | Intervention/Exposure; Health Status
564 | Unwin, DJ, Tobin, SD, Murray, SW, Delon, C, Brady, AJ. Substantial and sustained improvements in blood pressure, weight and lipid profiles from a carbohydrate restricted diet: An observational study of insulin resistant patients in primary care. International Journal of Environmental Research and Public Health. 2019. 16. doi:10.3390/ijerph16152680 | Intervention/Exposure
565 | Ushula TW, Mamun A, Darssan D, Wang WYS, Williams GM, Whiting SJ, Najman JM. Dietary patterns explaining variations in blood biomarkers in young adults are associated with the 30-year predicted cardiovascular disease risks in midlife: A follow-up study. | Size of Study Groups; Outcome
566 | Utari, A, Maududi, MS, Kusumawati, NRD, Mexitalia, M. Effects of low glycemic index diet on insulin resistance among obese adolescent with non-alcoholic fatty liver disease: A randomized controlled trial. Medical Journal of Indonesia. 2019. 28:123-128. doi:10.13181/mji.v28i2.2496 | Intervention/Exposure; Health Status
567 | Vahid F, Hoge A, Hébert JR, Bohn T. Association of diet quality indices with serum and metabolic biomarkers in participants of the ORISCAV-LUX-2 study. | Study Design
568 | Vahid, F, Goodarzi, R, Shivappa, N, Hébert, JR, Fazeli Moghadam, E. Dietary Inflammatory Index (DII®): A significant association between coronary heart disease and DII® in Armenian adults. European Journal of Preventive Cardiology. 2020. 27:2235-2237. doi:10.1177/2047487319880030 | Outcome; Publication Status
569 | Valerio J, Barabash A, Garcia de la Torre N, De Miguel P, Melero V, Del Valle L, Moraga I, Familiar C, Durán A, Torrejón MJ, Diaz A, Jiménez I, Matia P, Rubio MA, Calle-Pascual AL. The Relationship between Serum Adipokines, miR-222-3p, miR-103a-3p and Glucose Regulation in Pregnancy and Two to Three Years Post-Delivery in Women with Gestational Diabetes Mellitus Adhering to Mediterranean Diet Recommendations. 14. | Intervention/Exposure; Comparator
570 | Valsdottir, TD, Øvrebø, B, Kornfeldt, TM, Litleskare, S, Johansen, EI, Henriksen, C, Jensen, J. Effect of aerobic exercise and low-carbohydrate high-fat diet on glucose tolerance and android/gynoid fat in overweight/obese women: A randomized controlled trial. Frontiers in Physiology. 2023. 14. | Intervention/Exposure; Study Duration
571 | van Baak, MA, Roumans, NJT, Mariman, ECM. Diet Composition, Glucose Homeostasis, and Weight Regain in the YoYo Study. Nutrients. 2021. 13. doi:10.3390/nu13072257 | Intervention/Exposure
572 | van de Pas, KGH, Lubrecht, JW, Hesselink, ML, Winkens, B, van Dielen, FMH, Vreugdenhil, ACE. The Effect of a Multidisciplinary Lifestyle Intervention on Health Parameters in Children versus Adolescents with Severe Obesity. Nutrients. 2022. 14. | Study Design; Intervention/Exposure
573 | van Etten, S, Crielaard, L, Muilwijk, M, van Valkengoed, I, Snijder, MB, Stronks, K, Nicolaou, M. Lifestyle clusters related to type 2 diabetes and diabetes risk in a multi-ethnic population: The HELIUS study. Preventive Medicine. 2020. 137. doi:10.1016/j.ypmed.2020.106141 | Intervention/Exposure; Comparator
574 | van Poppel, MNM, Jelsma, JGM, Simmons, D, Devlieger, R, Jans, G, Galjaard, S, Corcoy, R, Adelantado, JM, Dunne, F, Harreiter, J, Kautzky-Willer, A, Damm, P, Mathiesen, ER, Jensen, DM, Andersen, LL, Tanvig, M, Lapolla, A, Dalfra, MG, Bertolotto, A, Wender-Ozegowska, E, Zawiejska, A, Hill, D, Desoye, G, J Snoek, F. Mediators of lifestyle behaviour changes in obese pregnant women. Secondary analyses from the DALI lifestyle randomised controlled trial. Nutrients. 2019. 11. doi:10.3390/nu11020311 | Intervention/Exposure; Outcome
575 | Vassou C, Yannakoulia M, Georgousopoulou EN, Chrysohoou C, Pitsavos C, Cropley M, Panagiotakos DB. Irrational Beliefs, Dietary Habits and 10-Year Incidence of Type 2 Diabetes; the ATTICA Epidemiological Study (2002-2012). 17. | Size of Study Groups
576 | Velázquez-López, L, Ponce-Martínez, X, Colín-Ramírez, E, Muñoz-Torres, AV, Escobedo-de la Peña, J. Un patrón dietético con alto contenido de lácteos enteros y bebidas azucaradas se asocia con la hemoglobina glicosilada y el peso en pacientes mexicanos con diabetes de tipo 2. A dietary pattern high in full-fat dairy and sweetened beverages is associated with glycated hemoglobin and weight in Mexican patients with type-2 diabetes. 2021. | Study Design; Health Status
577 | Vidal-Ostos, F, Ramos-Lopez, O, Jebb, SA, Papadaki, A, Pfeiffer, AFH, Handjieva-Darlenska, T, Kunešová, M, Blaak, EE, Astrup, A, Martinez, JA. Dietary protein and the glycemic index handle insulin resistance within a nutritional program for avoiding weight regain after energy-restricted induced weight loss. Nutrition and Metabolism. 2022. 19. | Intervention/Exposure
578 | Vinke PC, Navis G, Kromhout D, Corpeleijn E. Associations of Diet Quality and All-Cause Mortality Across Levels of Cardiometabolic Health and Disease: A 7.6-Year Prospective Analysis From the Dutch Lifelines Cohort. 44. | Outcome
579 | Virtanen, E, Kivela, J, Wikstrom, K, Lambrinou, CP, De Miguel-Etayo, P, Huys, N, Vrauko-Toth, K, Moreno, LA, Usheva, N, Chakarova, N, Rado, SA, Iotova, V, Makrilakis, K, Cardon, G, Liatis, S, Manios, Y, Lindstrom, J, Feel4Diabetes research, group. Feel4Diabetes healthy diet score: development and evaluation of clinical validity. BMC Endocr Disord. 2020. 20:46. doi:10.1186/s12902-020-0521-x | Outcome
580 | Vitale, M, Calabrese, I, Massimino, E, Shivappa, N, Hebert, JR, Auciello, S, Grioni, S, Krogh, V, Sartore, G, Signorini, S, Rivellese, AA, Riccardi, G, Vaccaro, O, Masulli, M. Dietary inflammatory index score, glucose control and cardiovascular risk factors profile in people with type 2 diabetes. International journal of food sciences and nutrition. 2021. 72:529. | Health Status
581 | Vitale, S, Mattioli, V, Shivappa, N, Hebert, JR, Palumbo, E, Porciello, G, Montagnese, C, Calabrese, I, Pica, R, Prete, M, Luongo, A, Grimaldi, M, Crispo, A, Falzone, L, Libra, M, Polesel, J, Serraino, D, Poletto, L, Martinuzzo, V, Gatti, D. The dietary inflammatory index in women diagnosed with breast cancer after 12 months of dietary. Treatment with a Mediterranean diet low in glycemic index: data from DEDICA randomized controlled trial. Nutrition, Metabolism & Cardiovascular Diseases. 2021. 31:3256-3256. doi:10.1016/j.numecd.2021.08.024 | Intervention/Exposure; Health Status; Publication Status
582 | Vizzari, G, Sommariva, MC, Cas, MD, Bertoli, S, Vizzuso, S, Radaelli, G, Battezzati, A, Paroni, R, Verduci, E. Circulating salicylic acid and metabolic profile after 1-year nutritional–behavioral intervention in children with obesity. Nutrients. 2019. 11. doi:10.3390/nu11051091 | Study Design; Intervention/Exposure
583 | Vizzuso, S, Amatruda, M, Banderali, G, Mameli, C, Zuccotti, G, Verduci, E. One year individual or group based lifestyle intervention in obese. Impact on metabolic profile and body composition. Obesity reviews. 2020. 21. doi:10.1111/obr.13118 | Study Design; Publication Status
584 | Vucic Lovrencic, M, Geric, M, Kosuta, I, Dragicevic, M, Garaj-Vrhovac, V, Gajski, G. Sex-specific effects of vegetarian diet on adiponectin levels and insulin sensitivity in healthy non-obese individuals. Nutrition. 2020. 79-80:110862. doi:10.1016/j.nut.2020.110862 | Study Design; Intervention/Exposure
585 | Wabo, TMC, Nkondjock, VRN, Onwuka, JU, Sun, C, Han, T, Sira, J. Association of fourteen years diet quality trajectories and type 2 diabetes mellitus with related biomarkers. Aging (Albany NY). 2021. 13:10112-10127. doi:10.18632/aging.202771 | Country
586 | Wagner, S, Lioret, S, Girerd, N, Duarte, K, Lamiral, Z, Bozec, E, Van den Berghe, L, Hoge, A, Donneau, AF, Boivin, JM, Merckle, L, Zannad, F, Laville, M, Rossignol, P, Nazare, JA. Association of Dietary Patterns Derived Using Reduced-Rank Regression With Subclinical Cardiovascular Damage According to Generation and Sex in the STANISLAS Cohort. J Am Heart Assoc. 2020. 9:e013836. doi:10.1161/JAHA.119.013836 | Outcome
587 | Wakasugi, M, Narita, I, Iseki, K, Asahi, K, Yamagata, K, Fujimoto, S, Moriyama, T, Konta, T, Tsuruya, K, Kasahara, M, Shibagaki, Y, Kondo, M, Watanabe, T. Healthy Lifestyle and Incident Hypertension and Diabetes in Participants with and without Chronic Kidney Disease: The Japan Specific Health Checkups (J-SHC) Study. Internal Medicine. 2022. 61:2841. | Intervention/Exposure
588 | Wang CR, Hu TY, Hao FB, Chen N, Peng Y, Wu JJ, Yang PF, Zhong GC. Type 2 diabetes prevention diet and all-cause and cause-specific mortality in the US population: a prospective study. | Outcome
589 | Wang DD, Qi Q, Wang Z, Usyk M, Sotres-Alvarez D, Mattei J, Tamez M, Gellman MD, Daviglus M, Hu FB, Stampfer MJ, Huttenhower C, Knight R, Burk RD, Kaplan RC. The Gut Microbiome Modifies the Association between a Mediterranean Diet and Diabetes in US Hispanic / Latino Population. | Study Duration
590 | Wang J, Lv S, Zhou Y, Sun Y, Zhu H, Yan G, Wu Y, Ma Y. The association between low carbohydrate diet scores and cardiometabolic risk factors in Chinese adults. | Study Design
591 | Wang J, Xie Z, Chen P, Wang Y, Li B, Dai F. Effect of dietary pattern on pregnant women with gestational diabetes mellitus and its clinical significance. 17. | Health Status
592 | Wang W, Lv J, Yu C, Guo Y, Pei P, Zhuang Z, Yang L, Millwood IY, Walters RG, Chen Y, Du H, Wu X, Chen J, Chen Z, Clarke R, Huang T, Li L. Lifestyle factors and fetal and childhood origins of type 2 diabetes: A prospective study of Chinese and European adults. | Intervention/Exposure
593 | Wang Y, Chen B, Zhang J, Li H, Zeng X, Zhang Z, Zhu Y, Li X, Hu A, Zhao Q, Yang W. Diets with higher insulinaemic potential are associated with increased risk of overall and cardiovascular disease-specific mortality. 128. | Outcome
594 | Wang Y, Chen B, Zhang J, Li H, Zeng X, Zhang Z, Zhu Y, Li X, Hu A, Zhao Q, Yang W. Diets with Higher Insulinemic Potential Are Associated with Increased Risk of Overall and Cardiovascular Disease-specific Mortality. | Outcome
595 | Wang Y, Xie W, Tian T, Zhang J, Zhu Q, Pan D, Xu D, Lu Y, Sun G, Dai Y. The Relationship between Dietary Patterns and High Blood Glucose among Adults Based on Structural Equation Modelling. 14. | Study Design
596 | Wang, DD, Qi, Q, Wang, Z, Usyk, M, Sotres-Alvarez, D, Mattei, J, Tamez, M, Gellman, MD, Daviglus, M, Hu, FB, Stampfer, MJ, Huttenhower, C, Knight, R, Burk, RD, Kaplan, RC. The Gut Microbiome Modifies the Association between a Mediterranean Diet and Diabetes in USA Hispanic/Latino Population. Journal of Clinical Endocrinology and Metabolism. 2022. 107:E924. | Study Design
597 | Wang, H, Wang, Y, Shi, Z, Zhao, L, Jian, W, Li, K, Xu, R, Wu, Y, Xu, F, Wang, Y, Peng, W. Association between Dietary Patterns and Metabolic Syndrome and Modification Effect of Altitude: A Cohort Study of Tibetan Adults in China. Nutrients. 2023. 15. | Outcome
598 | Wang, Z, Adair, LS, Cai, J, Gordon-Larsen, P, Siega-Riz, AM, Zhang, B, Popkin, BM. Diet quality is linked to insulin resistance among adults in China. Journal of Nutrition. 2017. 147:2102. | Country
599 | Watanabe, M, Sianoya, A, Mishima, R, Therdtatha, P, Rodriguez, A, Ramos, DC, Lee, YK, Dalmacio, LM, Nakayama, J. Gut microbiome status of urban and rural Filipino adults in relation to diet and metabolic disorders. FEMS microbiology letters. 2021. 368. | Study Design
600 | Wawro, N, Pestoni, G, Riedl, A, Breuninger, TA, Peters, A, Rathmann, W, Koenig, W, Huth, C, Meisinger, C, Rohrmann, S, Linseisen, J. Association of Dietary Patterns and Type-2 Diabetes Mellitus in Metabolically Homogeneous Subgroups in the KORA FF4 Study. Nutrients. 2020. 12. doi:10.3390/nu12061684 | Study Design
601 | Weston, LJ, Kim, H, Talegawkar, SA, Tucker, KL, Correa, A, Rebholz, CM. Plant-based diets and incident cardiovascular disease and all-cause mortality in African Americans: A cohort study. PLoS Medicine. 2022. 19. | Outcome
602 | White, SL, Flynn, AC, Poston, L. Impact of a positive or negative diagnosis of gestational diabetes and treatment, on weight change and dietary behaviour in an obese cohort: secondary analysis of the UK pregnancies better eating and activity trial (UPBEAT) randomised controlled trial (RCT). Diabetic medicine. 2019. 36:65-. doi:10.1111/dme.13883 | Publication Status
603 | Wilson, JE, Blizzard, L, Gall, SL, Magnussen, CG, Oddy, WH, Dwyer, T, Venn, AJ, Smith, KJ. An age- and sex-specific dietary guidelines index is a valid measure of diet quality in an Australian cohort during youth and adulthood. Nutrition Research. 2019. 65:43-53. doi:10.1016/j.nutres.2019.01.007 | Study Design
604 | Wong, JMW, Yu, S, Ma, C, Mehta, T, Dickinson, SL, Allison, DB, Heymsfield, SB, Ebbeling, CB, Ludwig, DS. Stimulated Insulin Secretion Predicts Changes in Body Composition Following Weight Loss in Adults with High BMI. The Journal of nutrition. 2021. | Intervention/Exposure
605 | Wu L, Ouyang J, Lai Y, Wu P, Wang Y, Ye Y, Wang J, Hu M, Zhang J, Xu J, Yang X, Yuan J, Zhao B, Song X, Yan S, Lv C, Liu G, Pan A, Pan XF. Combined healthy lifestyle in early pregnancy and risk of gestational diabetes mellitus: A prospective cohort study. | Intervention/Exposure
606 | Wu, S-L, Peng, L-Y, Chen, Y-M, Zeng, F-F, Zhuo, S-Y, Li, Y-B, Lu, W, Chen, P-Y, Ye, Y-B. Greater Adherence to Dietary Guidelines Associated with Reduced Risk of Cardiovascular Diseases in Chinese Patients with Type 2 Diabetes. Nutrients. 2022. 14. | Study Design; Health Status
607 | Wu, W, Tang, N, Zeng, J, Jing, J, Cai, L. Dietary Protein Patterns during Pregnancy Are Associated with Risk of Gestational Diabetes Mellitus in Chinese Pregnant Women. Nutrients. 2022. 14. | Study Design; Intervention/Exposure
608 | Wu, Y, Sun, G, Zhou, X, Zhong, C, Chen, R, Xiong, T, Li, Q, Yi, N, Xiong, G, Hao, L, Yang, N, Yang, X. Pregnancy dietary cholesterol intake, major dietary cholesterol sources, and the risk of gestational diabetes mellitus: A prospective cohort study. Clin Nutr. 2020. 39:1525-1534. doi:10.1016/j.clnu.2019.06.016 | Intervention/Exposure
609 | Würtz, AML, Jakobsen, MU, Bertoia, ML, Hou, T, Schmidt, EB, Willett, WC, Overvad, K, Sun, Q, Manson, JE, Hu, FB, Rimm, EB. Replacing the consumption of red meat with other major dietary protein sources and risk of type 2 diabetes mellitus: A prospective cohort study. American Journal of Clinical Nutrition. 2021. 113:612-621. doi:10.1093/ajcn/nqaa284 | Intervention/Exposure
610 | Xia Y, Cao L, Zhang Q, Liu L, Zhang S, Meng G, Wu H, Gu Y, Sun S, Wang X, Zhou M, Jia Q, Song K, Wu Q, Niu K, Zhao Y. Adherence to a vegetable dietary pattern attenuates the risk of non-alcoholic fatty liver disease on incident type 2 diabetes: the TCLSIH cohort study. | Health Status; Comparator
611 | Xiao, X, Qin, Z, Lv, X, Dai, Y, Ciren, Z, Yangla, Y, Zeng, P, Ma, Y, Li, X, Wang, L, Hu, Y, Yang, F, Fan, C, Tang, D, Dai, S, Zhang, N, Xie, X, Yin, J, Zhao, X. Dietary patterns and cardiometabolic risks in diverse less-developed ethnic minority regions: results from the China Multi-Ethnic Cohort (CMEC) Study. The Lancet Regional Health - Western Pacific. 2021. 15. | Study Design
612 | Xu, Yueqin, Li, Yan, Liang, Shuang, Li, Guimei. Differential analysis of nutrient intake, insulin resistance and lipid profiles between healthy and premature thelarche Chinese girls. Italian Journal of Pediatrics. 2019. 45:1-6. doi:10.1186/s13052-019-0758-z | Study Design; Intervention/Exposure
613 | Yabe, D, Kuwata, H, Fujiwara, Y, Sakaguchi, M, Moyama, S, Makabe, N, Murotani, K, Asano, H, Ito, S, Mishima, H, Takase, H, Ota, N, Seino, Y, Hamamoto, Y, Kurose, T, Seino, Y. Dietary instructions focusing on meal-sequence and nutritional balance for prediabetes subjects: An exploratory, cluster-randomized, prospective, open-label, clinical trial. J Diabetes Complications. 2019. 33:107450. doi:10.1016/j.jdiacomp.2019.107450 | Intervention/Exposure
614 | Yaegashi, A, Kimura, T, Hirata, T, Iso, H, Tamakoshi, A. Association between low-carbohydrate diet score and incidence of type 2 diabetes among Japanese adults: The JACC Study. Journal of Nutritional Science. 2023. 12. | Intervention/Exposure
615 | Yamada, Pamella, Paetow, Alexandra, Chan, Michael, Arslan, Alan, Landberg, Rikard, Young, BruceK. Pregnancy outcomes with differences in grain consumption: a randomized controlled trial. Journal of Perinatal Medicine. 2022. 50:411-418. doi:10.1515/jpm-2021-0479 | Intervention/Exposure
616 | Yamada, S, Inoue, G, Ooyane, H, Nishikawa, H. Changes in body weight, dysglycemia, and dyslipidemia after moderately low-carbohydrate diet education (Locabo challenge program) among workers in japan. Diabetes, Metabolic Syndrome and Obesity: Targets and Therapy. 2021. 14:2863-2870. doi:10.2147/DMSO.S317371 | Study Design; Intervention/Exposure
617 | Yan F, Eshak ES, Shirai K, Dong JY, Muraki I, Tamakoshi A, Iso H. Soy Intake and Risk of Type 2 Diabetes Among Japanese Men and Women: JACC Study. 8. | Intervention/Exposure
618 | Yang HJ, Kim MJ, Hur HJ, Jang DJ, Lee BK, Kim MS, Park S. Inverse Association of the Adequacy and Balance Scores in the Modified Healthy Eating Index with Type 2 Diabetes in Women. 15. | Study Design
619 | Yang J, Qian F, Chavarro JE, Ley SH, Tobias DK, Yeung E, Hinkle SN, Bao W, Li M, Liu A, Mills JL, Sun Q, Willett WC, Hu FB, Zhang C. Modifiable risk factors and long term risk of type 2 diabetes among individuals with a history of gestational diabetes mellitus: prospective cohort study. 378. | Intervention/Exposure
620 | Yang, R, Lv, J, Yu, C, et al. Importance of healthy lifestyle factors and ideal cardiovascular health metrics for risk of heart failure in Chinese adults. International Journal of Epidemiology. 2022. 51:567. | Intervention/Exposure; Outcome
621 | Yang, X, Li, Y, Wang, C, Mao, Z, Chen, Y, Ren, P, Fan, M, Cui, S, Niu, K, Gu, R, Li, L. Association of plant-based diet and type 2 diabetes mellitus in Chinese rural adults: The Henan Rural Cohort Study. Journal of Diabetes Investigation. 2021. 12:1569. | Study Design
622 | Yashpal S, Liese AD, Boucher BA, Wagenknecht LE, Haffner SM, Johnston LW, Bazinet RP, Rewers M, Rotter JI, Watkins SM, Hanley AJ. Metabolomic profiling of the Dietary Approaches to Stop Hypertension (DASH) diet provides novel insights for the nutritional epidemiology of type 2 diabetes mellitus (T2DM). | Intervention/Exposure; Outcome
623 | Yi SY, Steffen LM, Zhou X, Shikany JM, Jacobs DR Jr. Association of nut consumption with CVD risk factors in young to middle-aged adults: The Coronary Artery Risk Development in Young Adults (CARDIA) study. | Intervention/Exposure
624 | Yilmaz, S, Eskici, G, Mertoglu, C, Ayaz, A. Effect of different protein diets on weight loss, inflammatory markers, and cardiometabolic risk factors in obese women. Journal of Research in Medical Sciences. 2021. 26. | Study Design; Intervention/Exposure; Study Duration
625 | Yisahak, SF, Hinkle, SN, Mumford, SL, Li, M, Andriessen, VC, Grantz, KL, Zhang, C, Grewal, J. Vegetarian diets during pregnancy, and maternal and neonatal outcomes. Int J Epidemiol. 2021. 50:165-178. doi:10.1093/ije/dyaa200 | Intervention/Exposure
626 | Yokose, C, McCormick, N, Rai, SK, Lu, N, Curhan, G, Schwarzfuchs, D, Shai, I, Choi, HK. Effects of Low-Fat, Mediterranean, or Low-Carbohydrate Weight Loss Diets on Serum Urate and Cardiometabolic Risk Factors: A Secondary Analysis of the Dietary Intervention Randomized Controlled Trial (DIRECT). Diabetes Care. 2020. 43:2812-2820. doi:10.2337/dc20-1002 | Intervention/Exposure
627 | Yuan S, He J, Wu S, Zhang R, Qiao Z, Bian X, Wang H, Dou K. Trends in dietary patterns over the last decade and their association with long-term mortality in general US populations with undiagnosed and diagnosed diabetes. 13. | Outcome
628 | Yuste Gómez, A, Ramos Álvarez, MDP, Bartha, JL. Influence of Diet and Lifestyle on the Development of Gestational Diabetes Mellitus and on Perinatal Results. Nutrients. 2022. 14. | Intervention/Exposure
629 | Yuzbashian, E, Pakseresht, M, Vena, J, Chan, CB. Association of dairy consumption patterns with the incidence of type 2 diabetes: Findings from Alberta’s Tomorrow Project. Nutrition, Metabolism and Cardiovascular Diseases. 2022. | Intervention/Exposure
630 | Zamani, B, Milajerdi, A, Tehrani, H, Bellissimo, N, Brett, NR, Azadbakht, L. Association of a plant-based dietary pattern in relation to gestational diabetes mellitus. Nutr Diet. 2019. 76:589-596. doi:10.1111/1747-0080.12512 | Study Design
631 | Zhang B, Xu K, Mi B, Liu H, Wang Y, Huo Y, Ma L, Liu D, Jing H, Liu J, Cao S, Dang S, Yan H. Maternal Dietary Inflammatory Potential and Offspring Birth Outcomes in a Chinese Population. 153. | Study Design; Intervention/Exposure
632 | Zhang N, Zhou M, Li M, Ma G. Effects of Smartphone-Based Remote Interventions on Dietary Intake, Physical Activity, Weight Control, and Related Health Benefits Among the Older Population With Overweight and Obesity in China: Randomized Controlled Trial. 25. | Intervention/Exposure
633 | Zhang X, Xiao D, Guzman G, Edirisinghe I, Burton-Freeman B. Avocado consumption for 12 weeks and cardio-metabolic risk factors: a randomized controlled trial in adults with overweight or obesity and insulin resistance. | Intervention/Exposure
634 | Zhang Y, Wang Y, Zhang S, Zhang Y, Zhang Q. Complex Association Among Diet Styles, Sleep Patterns, and Obesity in Patients with Diabetes. 16. | Study Design; Health Status
635 | Zhang Z, Tabung FK, Jin Q, Curran G, Irvin VL, Shannon J, Velie EM, Manson JE, Simon MS, Vitolins M, Valencia CI, Snetselaar L, Jindal S, Schedin P. Diet-Driven Inflammation and Insulinemia and Risk of Interval Breast Cancer. | Outcome
636 | Zhang, C, Olsen, SF, Hinkle, SN, Gore-Langton, RE, Vaag, A, Grunnet, LG, Yeung, EH, Bao, W, Bowers, K, Liu, A, Mills, JL, Sherman, S, Gaskins, AJ, Ley, SH, Madsen, CM, Chavarro, JE, Hu, FB. Diabetes & Women’s Health (DWH) Study: An observational study of long-term health consequences of gestational diabetes, their determinants and underlying mechanisms in the USA and Denmark. BMJ Open. 2019. 9. doi:10.1136/bmjopen-2018-025517 | Intervention/Exposure
637 | Zhang, Shunming, Meng, Ge, Zhang, Qing, Liu, Li, Yao, Zhanxin, Wu, Hongmei, Gu, Yeqing, Wang, Yawen, Zhang, Tingjing, Wang, Xuena, Zhang, Juanjuan, Sun, Shaomei, Wang, Xing, Zhou, Ming, Jia, Qiyu, Song, Kun, Qi, Lu, Niu, Kaijun. Dietary fibre intake and risk of prediabetes in China: results from the Tianjin Chronic Low-grade Systemic Inflammation and Health (TCLSIH) Cohort Study. British Journal of Nutrition. 2022. 128:753-761. doi:10.1017/S0007114521003779 | Intervention/Exposure
638 | Zhang, Xiao, Gong, Yunhui, Della Corte, Karen, Yu, Dianke, Xue, Hongmei, Shan, Shufang, Tian, Guo, Liang, Yi, Zhang, Jieyi, He, Fang, Yang, Dagang, Zhou, Rong, Bao, Wei, Buyken, AnetteE, Cheng, Guo. Relevance of dietary glycemic index, glycemic load and fiber intake before and during pregnancy for the risk of gestational diabetes mellitus and maternal glucose homeostasis. Clinical Nutrition. 2021. 40:2791-2799. doi:10.1016/j.clnu.2021.03.041 | Intervention/Exposure
639 | Zhang, YZ, Zhou, L, Tian, L, Li, X, Zhang, G, Qin, JY, Zhang, DD, Fang, H. A mid-pregnancy risk prediction model for gestational diabetes mellitus based on the maternal status in combination with ultrasound and serological findings. Experimental and Therapeutic Medicine. 2020. 20:293-300. doi:10.3892/etm.2020.8690 | Intervention/Exposure
640 | Zhang, Z, Wu, Y, Zhong, C, Zhou, X, Liu, C, Li, Q, Chen, R, Gao, Q, Li, X, Zhang, H, Zhang, Y, Cui, W, Hao, L, Wei, S, Yang, X, Yang, N. Association between dietary inflammatory index and gestational diabetes mellitus risk in a prospective birth cohort study. Nutrition. 2021. 87-88:111193. doi:10.1016/j.nut.2021.111193 | Intervention/Exposure
641 | Zhao R, Zhou L, Lei G, Wang S, Li Y, Yang X, Xiong G, Hao L. Dietary Acid Load Is Positively Associated With Risk of Gestational Diabetes Mellitus in a Prospective Cohort of Chinese Pregnant Women. 9. | Intervention/Exposure
642 | Zheng, C, Shi, C, Bai, J, Shao, W, Zhang, C, Bu, J. Large-scale investigation on healthy status of teachers in Jiangsu Province, China. Progress in Nutrition. 2019. 21:294-298. doi:10.23751/pn.v21i2.6773 | Study Design
643 | Zhong, H, Penders, J, Shi, Z, Ren, H, Cai, K, Fang, C, Ding, Q, Thijs, C, Blaak, EE, Stehouwer, CDA, Xu, X, Yang, H, Wang, J, Wang, J, Jonkers, DMAE, Masclee, AAM, Brix, S, Li, J, Arts, ICW, Kristiansen, K. Impact of early events and lifestyle on the gut microbiota and metabolic phenotypes in young school-age children. Microbiome. 2019. 7. doi:10.1186/s40168-018-0608-z | Intervention/Exposure
644 | Zhou C, Liu C, Zhang Z, Liu M, Zhang Y, Li H, He P, Li Q, Qin X. Variety and quantity of dietary protein intake from different sources and risk of new-onset diabetes: a Nationwide Cohort Study in China. 20. | Intervention/Exposure
645 | Zhou, C, Zhang, Z, Liu, M, Zhang, Y, Li, H, He, P, Li, Q, Liu, C, Qin, X. Dietary carbohydrate intake and new-onset diabetes: A nationwide cohort study in China. Metabolism: Clinical and Experimental. 2021. 123. | Intervention/Exposure
646 | Zhou, J, Sheng, J, Fan, Y, Zhu, X, Wang, S. Dietary patterns, dietary intakes and the risk of type 2 diabetes: results from the Hefei Nutrition and Health Study. International journal of food sciences and nutrition. 2019. 70:412-420. doi:10.1080/09637486.2018.1515184 | Study Design
647 | Zhou, X, Chen, R, Zhong, C, Wu, J, Li, X, Li, Q, Cui, W, Yi, N, Xiao, M, Yin, H, Xiong, G, Han, W, Hao, L, Yang, X, Yang, N. Fresh fruit intake in pregnancy and association with gestational diabetes mellitus: A prospective cohort study. Nutrition. 2019. 60:129-135. doi:10.1016/j.nut.2018.09.022 | Intervention/Exposure
648 | Zhu Y. Are you what you eat? Through the lens of prepregnancy plant-based diets and risk of gestational diabetes. | Study Design; Publication Status
649 | Zhu, R, Fogelholm, M, Jalo, E, Poppitt, SD, Silvestre, MP, Møller, G, Huttunen-Lenz, M, Stratton, G, Sundvall, J, Macdonald, IA, Handjieva-Darlenska, T, Handjiev, S, Navas-Carretero, S, Martinez, JA, Muirhead, R, Brand-Miller, J, Raben, A. Animal-based food choice and associations with long-term weight maintenance and metabolic health after a large and rapid weight loss: The PREVIEW study. Clinical Nutrition. 2022. 41:817. | Intervention/Exposure
650 | Zhu, R, Fogelholm, M, Poppitt, SD, Silvestre, MP, Møller, G, Huttunen-Lenz, M, Stratton, G, Sundvall, J, Råman, L, Jalo, E, Taylor, MA, Macdonald, IA, Handjiev, S, Handjieva-Darlenska, T, Martinez, JA, Muirhead, R, Brand-Miller, J, Raben, A. Adherence to a plant-based diet and consumption of specific plant foods—associations with 3-year weight-loss maintenance and cardiometabolic risk factors: A secondary analysis of the preview intervention study. Nutrients. 2021. 13. | Size of Study Groups
651 | Zhu, Z, Li, F-R, Jia, Y, Li, Y, Guo, D, Chen, J, Tian, H, Yang, J, Yang, H-H, Chen, L-H, Zhang, K, Yang, P, Sun, L, Shi, M, Zhang, Y, Qin, L-Q, Chen, G-C. Association of Lifestyle With Incidence of Heart Failure According to Metabolic and Genetic Risk Status: A Population-Based Prospective Study. Circulation. Heart failure. 2022. 101161CIRCHEARTFAILURE122009592. | Outcome
652 | Zhuang, P, Zhang, Y, Mao, L, Wang, L, Wu, F, Cheng, L, Jiao, J. The association between consumption of monounsaturated fats from animal- v. plant-based foods and the risk of type 2 diabetes: a prospective nationwide cohort study. Br J Nutr. 2020. 1-10. doi:10.1017/S0007114520000677 | Intervention/Exposure
653 | Zinn, C, McPhee, J, Harris, N, Williden, M, Prendergast, K, Schofield, G. A 12-week low-carbohydrate, high-fat diet improves metabolic health outcomes over a control diet in a randomised controlled trial with overweight defence force personnel. Applied physiology, nutrition & metabolism. 2017. 42:1158-1164. doi:10.1139/apnm-2017-0260 | Intervention/Exposure; Publication Date