# Appendix 2 Conclusion statement from the existing systematic review

Table A 2 Conclusion statement from the existing systematic review for the research question: What is the relationship between dietary patterns consumed during pregnancy and risk of gestational diabetes mellitus?

Citation | Conclusion statement
Raghavan R, Dreibelbis C, Kingshipp BJ, Wong, YP, Terry N, Abrams B, Bartholomew A, Bodnar LM, Gernand A, Rasmussen K, Siega-Riz AM, Stang JS, Casavale KO, Spahn JM, Stoody E. Dietary Patterns before and during Pregnancy and Risk of Gestational Diabetes Mellitus: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0102 | Evidence is insufficient to estimate the association between dietary patterns during pregnancy and risk of gestational diabetes mellitus.