# References of the articles included in the systematic review

1 Ahern SM, Caton SJ, Blundell P, Hetherington MM. The root of the problem: increasing root vegetable intake in preschool children by repeated exposure and flavour flavour learning. Appetite. Sep 2014;80:154–60. doi:10.1016/j.appet.2014.04.016 24814221
2 Barends C, e Vries J, Mojet J, e Graaf C. Effects of repeated exposure to either vegetables or fruits on infant’s vegetable and fruit acceptance at the beginning of weaning. Food quality and preference. 2013;29:157–165. doi:10.1016/j.foodqual.2013.03.008
3 Barends C, e Vries JH, Mojet J, e Graaf C. Effects of starting weaning exclusively with vegetables on vegetable intake at the age of 12 and 23 months. Appetite. Oct 2014;81:193–9. doi:10.1016/j.appet.2014.06.023 24973508
4 Blomkvist EAM, Wills AK, Helland SH, Hillesund ER, Overby NC. Effectiveness of a kindergarten-based intervention to increase vegetable intake and reduce food neophobia amongst 1-year-old children: a cluster randomised controlled trial. Food Nutr Res. 2021;65 doi:10.29219/fnr.v65.7679
5 Caton SJ, Ahern SM, Remy E, Nicklaus S, Blundell P, Hetherington MM. Repetition counts: repeated exposure increases intake of a novel vegetable in UK pre-school children compared to flavour-flavour and flavour-nutrient learning. Br J Nutr. Jun 2013;109(11):2089–97. doi:10.1017/S0007114512004126 23110783
6 Coulthard H, Harris G, Fogel A. Exposure to vegetable variety in infants weaned at different ages. Appetite. Jul 2014;78:89–94. doi:10.1016/j.appet.2014.03.021 24685457
7 Dazeley P, Houston-Price C. Exposure to foods’ non-taste sensory properties. A nursery intervention to increase children’s willingness to try fruit and vegetables. Appetite. Jan 2015;84:1–6. doi:10.1016/j.appet.2014.08.040 25218879
8 Fildes A, Lopes C, Moreira P, . An exploratory trial of parental advice for increasing vegetable acceptance in infancy. Br J Nutr. Jul 2015;114:328–36. doi:10.1017/S0007114515001695 26063588
9 Forestell CA, Mennella JA. Early determinants of fruit and vegetable acceptance. Pediatrics. Dec 2007;120:1247–54. doi:10.1542/peds.2007-0858 18055673
10 Gerrish CJ, Mennella JA. Flavor variety enhances food acceptance in formula-fed infants. Am J Clin Nutr. Jun 2001;73:1080–5.11382663
11 Heath P, Houston-Price C, Kennedy OB. Let’s look at leeks! Picture books increase toddlers’ willingness to look at, taste and consume unfamiliar vegetables. Frontiers in psychology. 2014 2014;5 doi:10.3389/fpsyg.2014.00191
12 Hetherington MM, Schwartz C, Madrelle J, . A step-by-step introduction to vegetables at the beginning of complementary feeding. The effects of early and repeated exposure. Appetite. Jan 2015;84:280–90. doi:10.1016/j.appet.2014.10.014 25453593
13 Houston-Price C, Owen LH, Kennedy OB, Hill C. Parents’ experiences of introducing toddlers to fruits and vegetables through repeated exposure, with and without prior visual familiarization to foods: Evidence from daily diaries. Article. Food Quality and Preference. 2019;71:291–300.
14 Mennella JA, Nicklaus S, Jagolino AL, Yourshaw LM. Variety is the spice of life: strategies for promoting fruit and vegetable acceptance during infancy. Physiol Behav. Apr 22 2008;94:29–38. doi:10.1016/j.physbeh.2007.11.014 18222499
15 Owen LH, Kennedy OB, Hill C, Houston-Price C. Peas, please! Food familiarization through picture books helps parents introduce vegetables into preschoolers’ diets. Appetite. Sep 1 2018;128:32–43.29807124
16 Paul IM, Savage JS, Anzman SL, . Preventing obesity during infancy: a pilot study. Obesity (Silver Spring). Feb 2011;19:353–61. doi:10.1038/oby.2010.182 20725058
17 Remy E, Issanchou S, Chabanet C, Nicklaus S. Repeated exposure of infants at complementary feeding to a vegetable puree increases acceptance as effectively as flavor-flavor learning and more effectively than flavor-nutrient learning. J Nutr. Jul 2013;143:1194–200. doi:10.3945/jn.113.175646 23700337
18 Sullivan SA, Birch LL. Infant dietary experience and acceptance of solid foods. Pediatrics. Feb 1994;93:271–7.8121740
19 Birch LL, Gunder L, Grimm-Thomas K, Laing DG. Infants’ consumption of a new food enhances acceptance of similar foods. Appetite. Jun 1998;30:283–95. doi:10.1006/appe.1997.0146 9632459
20 Maier A, Chabanet C, Schaal B, Issanchou S, Leathwood P. Effects of repeated exposure on acceptance of initially disliked vegetables in 7-month old infants. Food Quality and Preference. 12// 2007;18:1023–1032. doi:10.1016/j.foodqual.2007.04.005
21 Houston-Price C, Butler L, Shiba P. Visual exposure impacts on toddlers’ willingness to taste fruits and vegetables. Journal article. Appetite. 2009;53(3):450–453.19744533
22 Anzman-Frasca S, Savage JS, Marini ME, Fisher JO, Birch LL. Repeated exposure and associative conditioning promote preschool children’s liking of vegetables. Appetite. Apr 2012;58:543–53. doi:10.1016/j.appet.2011.11.012 22120062
23 Bouhlal S, Issanchou S, Chabanet C, Nicklaus S. ‘Just a pinch of salt’. An experimental comparison of the effect of repeated exposure and flavor-flavor learning with salt or spice on vegetable acceptance in toddlers. Appetite. Dec 2014;83:209–217. doi:10.1016/j.appet.2014.07.032 25171850
24 Byrne E, Nitzke S. Preschool children’s acceptance of a novel vegetable following exposure to messages in a storybook. J Nutr Educ Behav. Jul–Aug 2002;34(4):211–3. doi:10.1016/s1499-4046(06)60095-x 12217264
25 Connell MLO, Henderson KE, Luedicke J, Schwartz MB. Repeated exposure in a natural setting: a preschool intervention to increase vegetable consumption. Journal of the Academy of Nutrition and Dietetics. Feb 2012 2012;112(2) doi:10.1016/j.jada.2011.10.003
26 Corsini N, Slater A, Harrison A, Cooke L, Cox DN. Rewards can be used effectively with repeated exposure to increase liking of vegetables in 4-6-year-old children. Journal article. Public health nutrition. 2013;16(5):942–951.21899792
27 Coulthard H, Williamson I, Palfreyman Z, Lyttle S. Evaluation of a pilot sensory play intervention to increase fruit acceptance in preschool children. Appetite. Jan 1 2018;120:609–615. doi:10.1016/j.appet.2017.10.011 29017905
28 de Wild VWT, de Graaf C, Jager G. Use of Different Vegetable Products to Increase Preschool-Aged Children’s Preference for and Intake of a Target Vegetable: A Randomized Controlled Trial. J Acad Nutr Diet. Jun 2017;117(6):859–866. doi:10.1016/j.jand.2016.11.006 28017593
29 Hausner H, Olsen A, Moller P. Mere exposure and flavour-flavour learning increase 2-3 year-old children’s acceptance of a novel vegetable. Appetite. Jun 2012;58(3):1152–9. doi:10.1016/j.appet.2012.03.009 22425616
30 Holley CE, Haycraft E, Farrow C. ‘Why don’t you try it again?’ A comparison of parent led, home based interventions aimed at increasing children’s consumption of a disliked vegetable. Appetite. Apr 2015;87:215–22. doi:10.1016/j.appet.2014.12.216 25555540
31 Hoppu U, Prinz M, Ojansivu P, Laaksonen O, Sandell MA. Impact of sensory-based food education in kindergarten on willingness to eat vegetables and berries. Food Nutr Res. 2015;59:28795. doi:10.3402/fnr.v59.28795 26652259
32 Karagiannaki K, Ritz C, Andreasen DS, . Optimising repeated exposure: Determining optimal stimulus shape for introducing a novel vegetable among children. Article. Foods. 2021;10(5)
33 Karagiannaki K, Ritz C, Jensen LGH, . Optimising Repeated Exposure: Determining Optimal Exposure Frequency for Introducing a Novel Vegetable among Children. Foods. Apr 21 2021;10(5)
34 Nekitsing C, Blundell-Birtill P, Cockroft JE, Fildes A, Hetherington MM. Increasing Intake of an Unfamiliar Vegetable in Preschool Children Through Learning Using Storybooks and Sensory Play: A Cluster Randomized Trial. J Acad Nutr Diet. Dec 2019;119(12):2014–2027.31378648
35 Nekitsing C, Blundell-Birtill P, Cockroft JE, Hetherington MM. Taste Exposure Increases Intake and Nutrition Education Increases Willingness to Try an Unfamiliar Vegetable in Preschool Children: A Cluster Randomized Trial. J Acad Nutr Diet. Dec 2019;119(12):2004–2013.31378647
36 van Belkom B, Umanets A, van Mil E, Havermans RC. Promoting vegetable acceptance in toddlers using a contingency management program: A cluster randomised trial. Article in Press. Appetite. 2023:106513. doi:10.1016/j.appet.2023.106513
37 Vandeweghe L, Verbeken S, Braet C, Loeys T, De Henauw S, Moens E. Strategies to increase preschoolers’ vegetable liking and consumption: The role of reward sensitivity. Article. Food Quality and Preference. 2018;66:153–159.
38 Wardle J, Cooke LJ, Gibson EL, Sapochnik M, Sheiham A, Lawson M. Increasing children’s acceptance of vegetables; a randomized trial of parent-led exposure. Appetite. Apr 2003;40:155–62.12781165
39 Zeinstra GG, Vrijhof M, Kremer S. Is repeated exposure the holy grail for increasing children’s vegetable intake? Lessons learned from a Dutch childcare intervention using various vegetable preparations. Appetite. Feb 1 2018;121:316–325.29158150
40 Masento NA, Dulay KM, Roberts AP, Harvey K, Messer D, Houston-Price C. See and Eat! The impact of repeated exposure to vegetable ebooks on young children’s vegetable acceptance. 182
41 Ramsay SA, Roe AJ, Davis JN, Price WJ, Johnson SL. Repeated exposures and child centered nutrition phrases increases young children’s consumption and liking of lentils. Article. Food Quality and Preference. 2017;62:317–322.