# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between repeated exposure to foods and food acceptance?” with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Infants and young children (birth to 24 months)

Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

Repeated taste exposure to a single fruit is likely to increase acceptance of the target fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

Repeated taste exposure to a vegetable is likely to increase acceptance of a different vegetable, but not a fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

Repeated taste exposure to a fruit may increase acceptance of a different fruit, but not a vegetable, by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

A conclusion statement cannot be drawn about the effect of repeated non-taste exposure, either alone or together with taste exposure, on food acceptance by infants and young children ages 4 to 24 months because there are substantial concerns with consistency and directness in the body of evidence. (Grade: Grade Not Assignable)

### Young children (2 to 6 years)

Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by children ages 2 to 6 years. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

A conclusion statement cannot be drawn about the effect of repeated taste exposure to fruit(s) on acceptance of target fruit(s) by children ages 2 to 6 years because there is no evidence available. (Grade: Grade Not Assignable)

Repeated taste exposure to a target vegetable may increase acceptance of a different vegetable by children ages 2 to 6 years. This conclusion statement is based on evidence on evidence graded as limited. (Grade: Limited)

A conclusion statement cannot be drawn about the effect of repeated taste exposure to a target fruit on acceptance of a different fruit by children ages 2 to 6 years because there is no evidence available. (Grade: Grade Not Assignable)

Repeated non-taste exposure alone or together with taste exposure to a target fruit or vegetable increases acceptance, specifically willingness to try, of the target fruit or vegetable by children ages 2 to 6 years. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

## Research recommendations

This body of evidence had certain limitations that yield areas for further research, including:

- Conduct research with samples representing more diverse populations in terms race, ethnicity and socioeconomic position. Studies conducted within the United States are also needed to examine the association of interest within the context of U.S. dietary patterns and cultural influences around eating.
- Characterize how repeated exposure to various textures (pureed vs diced/lumpy) affects food acceptance: most of this evidence is in younger infants using pureed foods; within-subject, cross-over design studies are needed to test textural differences (which can impact other sensory properties such as appearance and flavor) on food acceptance.
- Examine different modes of food preparation, with specific focus on homemade foods: this body of evidence was largely based on manufactured baby food purees. Research is needed to determine how to best facilitate transition to healthier table foods. Of the limited evidence available, it appears the babies do not generalize from manufactured foods to homemade foods; thus research is needed to determine if there is difference in transition to healthier table foods after early exposure to homemade purees compared to commercial baby food purees.
- Examine relationships between repeated exposure and acceptance to a wider range of fruits and vegetables than represented in the current body of evidence, including cultural foods and other food groups, specifically meats. Emerging research recommends pureed meats as a first food and therefore it is important to understand how repeated exposure to meat influences food acceptance patterns during complementary feeding.
- Conduct research on the mechanisms of flavor generalization: research is needed to determine what aspects of diverse flavor experiences impact acceptance of a novel flavor.
- Identify whether there are critical windows for repeated food exposure, specifically whether early repeated exposure during infancy and prior to the emergence of neophobia has protective effects on food acceptance and diet quality in later childhood.
- Examine the pathway of flavor exposure from birthing parent and human milk feeding on infant and child’s food acceptability.
- Evaluate whether adjunct strategies (e.g., social modeling, praise, sensory play) can facilitate acceptance in cases where repeated taste exposure alone is not sufficient to produce acceptance. Evidence shows variability in effects of repeated exposure on acceptance, suggesting that repeated exposure may be more effective for some children than others and for some foods more than others. Research is needed to determine whether adjunct strategies designed to enhance children’s experience with new/disliked foods (i.e., make foods more pleasant) may be helpful in cases where repeated exposure alone is not sufficient to produce acceptance.
- Evaluate within and between child variation in the feasibility and effectiveness of repeated exposure on food acceptance—whether different patterns are observed based on child temperament and age as well as social, structural, and environmental influences such as food parenting, availability of and access to healthful foods, and socio-economic resources.
- Determine how parent-child interactions during feeding facilitate the acceptability of healthy foods. Specifically, the extent to which effects of repeated exposure are dependent on and/or facilitated by responsive feeding.

Table 13 Evidence examining the relationship between repeated food exposure and food acceptance in infants and young children (birth to 24 months)^a^

Study Information | Intervention, Comparator, Outcome | Results
[underlined: Ahern, 2014]^1^; RCT, within-subjects, U.K.; Baseline N: 42; Analytic N: 29 (n=28 at 1 mo, n=10 at 6 mo); Power analysis: NR; Child characteristics:; - Age: 15-56 mo; - Female: NR; - Race/ethnicity: NR; Caregiver characteristics:; - Female: NR; - Age: NR; - Race/ethnicity: NR; - SEP: NR; Setting: Day care centers; Study objective and primary outcomes: To investigate the effectiveness of repeated exposure and flavor–flavor learning for increasing vegetable intake and liking in preschool children. Primary outcomes: vegetable intake and liking | Target and test foods: celeriac, swede, or turnip puree (novel foods); Repeat exposure: Taste; 2-3/ wk, 3-4 wks, 6-8 exposures; Children received 6-8 exposures to a flavor-flavor learning (FFL) (vegetable with added applesauce) variant of 1 of the vegetable purees, 6-8 exposures to a RE variant of another of the vegetable purees (a total of 2 or 3 exposures per week). No exposure was given to the third (control) vegetable. Vegetables were lab-made, 100g/pot, max 2 pots offered, children could consume as much or as little they wanted.; Intervention/control groups:; - Repeated exposure (RE): Children received 6-8 exposures of basic vegetable puree; - Flavor-flavor learning (FFL): all children fed 6-8 exposures of vegetable puree with added applesauce; - Control vegetables: Novel vegetable puree; (during pre-test and post-test); Outcomes and assessment methods:; - Weighed intake; - Timing of assessment: Baseline, post-intervention, 1 mo and 6 mo follow-up | [underlined: Intake (g) pre- and post-intervention]; Main effect of vegetable: chi-sq(2) = 25.97, p < 0.001 swede and turnip ↑ vs celeriac; Main effect of age group: chi-sq(1) = 8.81, p < 0.01; Interaction of time by age group: chi-sq(3) = 36.85, p < 0.001; vegetable puree in children in the older age group (≥24 m) ↓ vs younger group (immediately post-intervention and at follow-up); [underlined: Intake across exposures]; Main effect of exposures: chi-sq(7) = 63.16, p < 0.001; vegetable puree in later trials ↑ than earlier trials; A significant increase in intake was identified by exposure 3, and no further significant increase was found after the third exposure.; Main effect of condition: NS; Interaction of exposures and condition: chi-sq(7) = 16.54, p < 0.05; Intake across exposures in the FFL condition ↑; Main effect of age group: chi-sq(1) = 5.83, p < 0.05; Interaction of exposures by age group: chi-sq(7) = 32.32, p < 0.001; Intake in younger children (< 24mo) ↑ compared to older children (≥24mo) across the intervention.; Intake in older children (≥24mo) ↓ compared to younger children (< 24mo) in the later trials.; [underlined: Correlation between intervention and control groups]:; Post intervention intake: all conditions correlated (RE and FFL: r = 0.63, p < 0.001; RE and control: r = 0.65, p < 0.001; FFL and control: r = 0.64, p < 0.001),; Change in intake across conditions: all conditions correlated (RE and FFL: r = 0.51, p < 0.01; RE and control: r = 0.47, p < 0.01; FFL and control: r = 0.76, p < 0.001) suggesting that a child whose intake increased in 1 condition was likely to eat more in all conditions.; Model adjustments: Condition, time, age group, and identify of the vegetable.; Funding source(s): European Community’s Seventh Framework Programme
Barends, 2013^2^; RCT parallel design, The Netherlands; Baseline N: 101; Analytic N=99; Power analysis: NR; Barends, 2014^3^; RCT parallel design, The Netherlands; Baseline: N=101; Analytic N=84 (N=81 at 18 mo); Child characteristics:; - Age: ~ 5.4 mo; - Female: 49%; - Race/ethnicity: NR; Caregiver characteristics:; - Female: NR; - Age: ~31 y; - Race/ethnicity: NR; - Education: low 17%, middle 32% high 50%; Setting: Home (testing in lab); Objective and primary outcomes: To assess the effect of weaning exclusively with vegetables as compared to weaning exclusively with fruit on the acceptance of fruit and vegetables after 19 days intervention period. Primary outcome: vegetable intake | Target and test foods: Green beans and apple puree (commonly consumed) and artichoke and plum puree (less commonly consumed), Commercially available; Repeat exposure: Taste; 1/d every other day for 14d; 7 exposures.; Infants fed a variety of 3 purees at home days 3-16 (assigned puree every other day and other purees on alternate days). Offered 125g serving (plum= 100g) and fed until rejected more than 3 successive times; Intervention/control groups:; - Green bean group: Infants fed manufactured green bean puree every other day (7 days), and on alternate days offered manufactured broccoli (4 days) or cauliflower purees (3 days), n=24; - Artichoke group: Infants fed manufactured artichoke puree every other day (7 days), and on alternate days offered broccoli (4 days) or cauliflower (3 days), n=27; - Apple group: Infants fed manufactured apple puree every other day (7 days), and on alternate days offered banana (4 days) or pears (3 days), n=24; - Plum group: Infants fed manufactured plum puree every other day (7 days), and on alternate days offered banana (4 days) or pears (3 days), n=24; - Control (comp): the fruit or vegetable not provided during exposure period, depending on group (either green bean, artichoke, apple, or plum puree); Outcomes and assessment methods:; - Weighed intake and maternal perceptions of infant liking (9-point scale); - Assessment timing: Days 1 and 2 and 18 and 19, food order counterbalanced on consecutive days;; - Barends, 2014: 6 month and 18-month follow-up | [underlined: Intake at pre- and post-intervention and change in intake (g/d), Mean] [underlined: (SD)]; Green bean (int) vs Artichoke (comp) intake; Green bean: Pre 24 (22) vs Post 59 (70), p=0.016 ↑ Artichoke: Pre 26 (23) vs Post 43 (42), p=0.042 ↑; Change in intake: Green beans 35.20 (65.99) vs artichoke 17.75 (40.33), p=0.125; Artichoke (int) vs green bean (comp) intake; Artichoke: Pre 24 (40) vs Post 27 (19), p=0.603; Green bean: Pre 21 (31) vs Post 50 (53), p<0.001 ↑; Change in intake: Artichoke vs green bean: NS; Apple (int) vs plum (comp) intake; Apple: Pre 53 (53) vs Post 66 (56), p=0.103; Plum: Pre 47 (43) vs Post 51 (35), p=0.698; Change in apple vs change in plum: NS; Plum (int) vs apple (comp) intake; Plum: Pre 37 (35) vs Post 75 (50), p<0.001 ↑; Apple: Pre 43 (43) vs Post 70 (43), p<0.033 ↑; Change in apple vs change in plums: NS; [underlined: Infant’s liking (maternal report) pre- versus post-intervention (9-point scale), Mean (SD)]; Green bean (int) vs Artichoke (comp) maternal rating of infant enjoyment; Green bean: Pre 5.4 (1.9) vs Post 6.2(1.8), p= 0.049 ↑; Artichoke: Pre 5.3 (2.0) vs Post 5.4 (1.7), p= 0.806; Artichoke (int) vs green bean (comp) maternal rating of infant enjoyment; Artichoke: Pre 4.8 (2.2) vs Post 5.2 (1.8), p= 0.284; Green bean: Pre 4.6 (2.2) vs Post 6.2 (1.6), p=0.003 ↑; Apple (int) vs plums (comp) maternal rating of infant enjoyment; Apple: Pre 5.8 (2.1) vs Post 6.4 (1.2), p= 0.110; Plum: Pre 5.9 (1.9) vs Post 6.5 (1.3), p= 0.200; Plum (int) vs apple (comp) maternal rating of enjoyment; Plum: 5.7 (1.9) vs 7.0 (0.6), p= 0.001 ↑; Apple liking: 6.1 (1.6) vs 6.8 (1.0), p= 0.074; Green bean intake after repeated exposure to fruit (g/d), Mean (SD); Vegetable groups Day 1 or 2: 23 (27) vs Fruit groups Day 19: 24 (29), p=0.814; Apple intake after repeated exposure to vegetables (g/d), Mean (SD); Fruit groups Day 1 or 2: 45 (49) vs Vegetable groups Day 19: 47 (48), p=0.842; Green bean intake, between group (vegetable versus fruit group); 6 mo follow-up: vegetable group (106 ± 109 g) and fruit group (93 ± 94 g; P = 0.62, ND; 18 mo follow-up: vegetable group (47 ± 75 g) and fruit group (42 ± 74 g; P = 0.73), ND.; Apple intake, between group (vegetable versus fruit group); 6 mo follow-up: vegetable group (151 ± 107g) and fruit group (174 ± 98g), P = 0.30), ND; 18 mo follow-up: vegetable group (156 ± 108 g) and fruit group (175 ± 111 g), P = 0.61), ND; Model adjustments: None; Funding source (s): Wageningen University and Research Centre
[underlined: Caton, 2013]^5^; RCT parallel design, U.K.; Baseline N=88; Analytic N=72 (N=45 at 5 wk); Power calculation: NR; Child characteristics:; - Age: ~23.6 mo; - Female: 56%; - Race/ethnicity: NR; Caregiver characteristics:; - Female: NR; - Age: NR; - Race/ethnicity: NR; - SEP: NR; Setting: Pre-school; Objective and primary outcomes: To compare the effectiveness of different learning strategies (FFL, FNL) with repeated taste exposure on increasing intake of a novel vegetable. Primary outcomes: intake of novel vegetable | Target food/Test food: Artichoke (low familiarity/low consumption) and carrot (test vegetable); Repeated Exposure: Taste, 1/d, 10d, 10 exposures. Children offered 200g of artichoke and could consume as much or as little as they like; post-intervention artichoke offered 1 time/wk during wk 3 and 4.; Commercial carrot puree baby food served as control (pre- and post- exposure) for all conditions.; Intervention/control groups:; - Repeated exposure (RE): Plain artichoke puree (lab-made), fed for 10 days, n=22; - Flavor-flavor learning (FFL): Artichoke puree + sucrose (lab-made), fed for 10 days, n=25; - Flavor-nutrient learning (FNL): Artichoke puree + sunflower oil (lab-made), fed for 10 days, n=25; Outcomes and assessment methods:; - Weighed intake (order counterbalanced); - Assessment timing: pre/post-intervention and 5 wk post-intervention. | [underlined: Intake, change pre- to post-exposure (g), Mean (SEM)]; Artichoke (int) vs carrot (comp) intake, 69g (8.7) vs 29g (7.2), p=0.001 ↑; From pre- to post-exposure intake of both artichoke and carrots increased (p=0.001) (with and without control for baseline carrot intake); [underlined: Intake, change pre- to post-exposure by exposure (RE/FFL/FNL) (g), Mean (SEM)]; RE 65.3 (7.4), FNL 52.3 (6.9), and FFL 60.9 (6.9), NS (data reported graphically); [underlined: Number of exposures]; A main effect of exposure number was observed (p=0.001) with no effect of condition.; Intake during exposures 5, 6, 7, 8, 9 and 10 was significantly higher than intake during exposure 1 (p=0.005) ↑;; There was no difference in intake in exposures 5 through 10.; [underlined: Intake pre-, post- and 5 wk post-intervention, Mean (SD)]; Change in intake by condition (g), Mean (SEM); Significant time*condition [underlined: (RE/FFL/FNL)] interaction indicating greater intake of artichoke in the RE condition at post-test and follow-up (p=0.02) ↑; [underlined: Vegetable intake (g) pre- and post-intervention by age (≤ 23 mo; 24 – 38 mo), Mean, (SEM)]; No significant effect of age on baseline intake (p=0.1), age by condition (p=0.9), and age by condition by vegetable interactions (p=0.2); Pre-intervention: Younger: 61.7 (6.9) vs older: 39.1 (10.7), p=0.002 ↑; Post-exposure: Younger: 129.2 (12.21) vs Older: 65.6 (13.6); p=0.002 ↑; [underlined: Vegetable intake, change pre- to post-intervention (g), Mean (SD)]; Artichoke 66.5 (8.4) vs carrot 27.4 (7.2), p=0.001 ↑; Younger 67.5 (8.6) vs Older 26.4 (9·6); No interaction with age or condition; Model adjustments: Baseline carrot intake (pre/post change in intake); Funding source(s): European Community’s Seventh Framework Programme.
Coulthard, 2014^6^; RCT parallel design, U.K.; Baseline N: 77; Analytic N=60; Power analysis: Based on findings from Maier et. al. (2008) calculated minimum number of participants in each group, n=13; Child characteristics:; - Age: 5.18 ± 0.84 mo; - Female: 47%; - Race/ethnicity: NR; Caregiver characteristics:; - Female: 100%; - Age: ~32 y; - Race/ethnicity: NR; - Education: ~15.9 y; - SEP: Recruited from inner city area with mixed ethnicity and social groups; Setting: Home; Objective and primary outcomes: To examine efficacy of exposure to variety in infants. Primary outcomes: intake of target vegetable | Target/test foods:; Carrot, parsnip, courgetti [zucchini], or sweet potato (test foods) pea (target food); lab-made; Repeat exposure: Taste; 1/d for 9d; 9 exposures.; Infants fed in usual way until 3 refusals; amount of test food provided for each infant was 200g; maternal report of food diary to measure compliance.; Intervention/control groups:; - Single taste group (early complementary feeding (CF) group n=15; later CF group n=15): carrot puree for 9 consecutive days; - Variety group (early CF group n=14; later CF group n=16): 1 vegetable/day (parsnip, courgetti [zucchini], or sweet potato) with daily changes for 9 consecutive days (each food given for 3 days); Outcomes and assessment methods:; - Weighed intake; - Assessment timing: Day 11 | [underlined: Pea intake post-intervention, stratified by CF group, Mean (SE)]; Single vs variety group; Early CF group: 41.13 (6.40) vs 35.77 (6.88), p>0.05; Later CF group: 22.62 (6.20) vs 45.64 (6.63), p<0.05; Model adjustments: None; Funding source(s): Feeding for Life Foundation
[underlined: Fildes, 2015]^8^; RCT Parallel Design, U.K., Greece, and Portugal Baseline N=146; Analytic N=139; Power assessment: n=120 for 80% power to detect a medium effect size (d=0.5) at P=0.05; Child characteristics:; - Age: 5.2 ± 0.6 mo; - Female: 47.5%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: 33 ± 4.7 y; - Female: 100%; - Marital status (married): 93.5%; - Education: Below University (26.6%), Undergraduate or above (73.4%); Marital status: Married/cohabiting (93.5%), Single (6.5%); Setting: Home (testing in hospital); Objective and primary outcomes: To investigate the impact of advising parents to introduce a variety of single vegetables as first foods on infants’ subsequent acceptance of a novel vegetable. Primary outcomes: fruit and vegetable intake and liking | Target/test food: specific test vegetables and fruit NR (novel, selected by mother) artichoke purée unfamiliar vegetable (target vegetable); peach purée, unfamiliar fruit (test fruit) Commercially available.; Repeated exposure: Taste; 1/d; repeated 3 times over 15d; 15 exposures.; Five vegetables were selected by mother as the first foods to be introduced in sequence for 15 d. For a further 5 d, vegetables were continued to be offered, but in addition with additional age-appropriate foods being introduced. At follow-up, taste tests were administered with unfamiliar vegetable and unfamiliar fruit (130g jars) and mothers were instructed to feed their infant as they normally would until infant refused on 3 or more occasions or finished 2 full jars. Vegetable always offered first, followed by fruit 10 min later.; Intervention/control groups:; - Intervention: received verbal and written guidance to introduce 5 vegetables, 1 per d in a specific order (A, B, C, D, E), as first foods, repeated over 15d; they were provided with manufactured vegetable purees but were told they could prepare their own, n=71; - Control: country-specific ‘usual care’ (varies between countries), no guidance on vegetable introduction provided, n=68; Outcomes and assessment methods:; - Weighed intake; mothers and unblinded researchers’ perception of infant liking (9-point scale).; - Assessment timing: baseline and 1-month (after the introduction of solid foods) follow-up | [underlined: Intake, group differences, intervention versus control group, Mean (g):]; Vegetable intake: 38·91 vs. 29·84, p=0.064, NS.; Mother’s rating vegetable liking: 5.34 vs. 4.5, P=0·052, NS; Researcher’s rating vegetable liking: ↑ 5.38 vs. 4.51, P=0·032; Fruit intake: 51.18 vs. 64.23, p=0.211, NS.; Mother’s rating fruit liking: 6.20 vs. 6.57, P=0·371, NS; Researcher rated fruit liking: 6.07 vs. 6.46, P=0·327, NS; [underlined: Intake, main effects of intervention (intervention versus control)]; Vegetable intake: No main effect, P=0·064, NS.; Researcher rated veg liking: P=0·032,; Maternal rated veg liking, P=0·052; Intake and liking for fruit: No main effect, NR; [underlined: Separate analyses by country]; U.K., intervention vs. control:; Vegetable intake: 32·8 vs. 16·5 g, P=0·003 ↑; Cohen’s d = 0·8; Mother rated veg liking: 6·7 vs. 4·3, P=0·001 ↑,; Researchers rated veg liking: 6·7 vs. 4·6, P=0·001 ↑; Cohen’s d = 0·8 for both.; Fruit intake: 27·9 vs. 40·7 g, P=0.144, NS;; Mother’s rated fruit liking: 6.69 vs. 7.25, P=0.352, NS; Researcher’s rating fruit liking: 6.97 vs. 7.29, P=0.55, NS; Greek, intervention vs. control:; Vegetable intake: 36·3 vs. 23·6 g, P=0.187, NS; Mother rates veg liking: 4·3 vs. 3·3, P=0.3, NS; Researcher rated veg liking: 4·6 vs. 3·4, P=0.123, NS; Fruit intake: 82.5 g vs. 58.4 g, P=0.272, NS; Mother rated fruit liking: 6.0 vs. 5.2, P=0.428, NS; Researcher rated fruit liking: 5.88 vs. 5.13, P=0.4, NS); Portugal, intervention vs. control; Vegetable intake: 46·9 v. 45·1 g, P=0.87, NS; Mother rated veg liking: 4·6 vs. 5·2, P=0.412, NS; Researchers rated veg liking: 4·5 vs. 5·0, P=0.54, NS.; Fruit intake: 56.74 vs. 88.36, P=0.98, NS; Mother’s rated fruit liking: 5.85 vs. 6.68, P=0.273, NS; Researcher fruit liking: 5.3 vs. 6.39, P=0.095, NS); Model adjustments: primary analysis adjusted for country; secondary analysis by country.; Funding source(s): European Community’s Seventh Framework Programme (FP7/2007-2013) under the grant agreement no. 245012-HabEat. The pureés were donated by Danone Nutricia Research.
[underlined: Forestell, 2007]^9^; RCT parallel design, USA; Baseline N=45; Analytic N=34; Power analysis: NR; Child characteristics:; - Age: ~5.8 mo; - Female: 46.7%; - Race/ethnicity: NR; Caregiver characteristics:; - Age ~31.8 y; - Female: 100%; - Race/ethnicity: White: 45.5%, Black: 36.4%, Hispanic 6.8%,; Other/Mixed Ethnicity: 11.4%; - Education: Mean years of schooling: 14.8; Had some college education: 26.7%.; - SEP: WIC participants: 44.4%; Setting: Home (testing in lab); Objective and primary outcomes: To elucidate some of the factors that contribute to acceptance of a green vegetable and a fruit initially and after different types of dietary exposure. Primary outcomes include a variety of food acceptance measures. | Target/test food: Manufactured green bean puree and peach puree fed until the child rejected the food ≥3 consecutive times or finished 2 jars.; Repeated exposure: Taste; 1/d for 8 d (consecutive); 8 exposures fed until the child rejected the food ≥3 consecutive times or finished 2 jar (green beans, ~113 g; peaches, ~99g); Intervention and Control groups:; - GB group: fed manufactured green bean puree, n=16; - GB-P group: fed manufactured green bean puree and then manufactured peach puree (within 1 hr), n=29; Outcomes and assessment methods:; - Weighed intake; mothers’ perception of infant enjoyment of food assessed (9-point scale); infants’ facial response captured through video monitoring of feeding sessions, coded by trained blinded assessors; time of feeding duration (offered until infant refused food 3 consecutive times or finished contents of 2 jars); rate of feeding; - Assessment timing: pre- and post-intervention | Green beans; [underlined: Intake of green bean puree (g), Mean (SEM)]; GB group: before 65.3 (12.5), after 97.5 (17.3), p<0.05; GB-P group: before 52.3 (9.0), after 91.6 (12.4), p<0.05; Both groups: before 56.8 (7.3), after 93.6 (10.0), p<0.05; [underlined: Rate of consumption (g/min), Mean (SEM)]; GB group: before 4.8 (0.8), after 6.6 (1.0), p<0.05; GB-P group: before 3.9 (0.5), after 6.3 (0.7), p<0.05; Both groups: before 4.5 (0.4), after 5.8 (0.4), p<0.05; [underlined: Mothers’ rating of infants’ liking (9-point scale), Mean (SEM)]; GB group: before 6.4 (0.5), after 6.9 (0.6), NS; GB-P group: before 7.1 (0.4), after 6.9 (0.4), NS; Both groups: before 6.9 (0.3), after 6.9 (0.3), NS; [underlined: Frequency of distaste facial expressions while eating green beans scored by trained coders, Means NR before vs after exposure:]; GB group: No difference in facial distaste expression; GB-P group: Showed less negative expressions after the intervention (fewer brow movements), p<0.01; fewer squints, p<0.003; fewer upper-lip raises, p<0.02; Peaches; [underlined: Intake of peach puree (g), Mean (SEM)]; GB group: before 70.9 (14.0), after 74.7 (15.1), NS; GB-P group: before 67.7 (10.4), after 79.2 (11.2), NS; ND in peach intake from before to after the intervention in either group; [underlined: Rate of consumption (g/min), Mean (SEM)]; GB group: before 4.8 (0.7), after 5.8 (0.8), p<0.05; GB-P group: before 4.4 (0.5), after 5.9 (0.6), p<0.05; Both groups: before 4.5 (0.4), after 5.8 (0.4), p<0.05; [underlined: Mothers’ rating of infants’ liking (9-point scale), Mean (SEM)]; GB group: before 6.8 (0.5), after 6.6 (0.6), NS; GB-P group: before 7.1 (0.4), after 6.9 (0.5), NS; Both groups: before 7.0 (0.3), after 6.4 (0.4), NS; Model adjustments: None; Funding source(s): NIH
[underlined: Gerrish, 2000]^10^; RCT parallel design, USA; Baseline N=48; Analytic: N=48; Power analysis: NR; Child characteristics:; - Age: ~ 4.6 mo; - Female: 50%; - Race/ethnicity: 45.8% African American, 39.6% white, 2.1% Hispanic, and 12.5% other; Caregiver characteristics:; - Age ~27.6 y; - Female: 100%; - Race/ethnicity: 45.8% African American, 39.6% white, 2.1% Hispanic, and 12.5% other; - SEP: NR; Setting: Home (testing in lab); Objective and primary outcomes: To examine whether acceptance of novel foods (carrots, chicken) by formula-fed infants could be facilitated by providing infants with carrots, potatoes, or a variety of vegetables when solid foods are introduced; and examine whether infants who had previously consumed fruit would be less likely to reject vegetables when first introduced than would infants without such experience. | Target food/ Test food: carrot, chicken (target food; novel foods; commercial stage 1); Carrot, Potato, Pea, Squash (test foods, commercial stage 1); Repeated Exposure: Taste; 1/d, 9 exposures over 12 days; Fed (71g jar) until the infant refused the spoonful of food on ≥3 consecutive occasions.; Intervention and Control groups:; - Carrot group: mothers fed manufactured carrot puree 1/d over 9d, n=16; - Potato group: mothers fed manufactured potato puree 1/d over 9d, n=16; - Vegetable variety group: mothers fed 1 manufactured vegetable puree per day over 9d, vegetables included pea, potato, and squash, in rotating order, each fed 3 times, n=16 (Note: did not include carrots); Outcomes and assessment methods:; - Weighed intake; duration of feeding; rate of feeding assessed via videotapes by blind observers; maternal perception of infant liking; - Assessment timing: Pre/Post intervention (carrot), post-intervention (day 12; chicken) | Carrot; [underlined: Intake pre- and post-intervention (g) Mean, SD:]; Carrot group: before 50.3 (5.8), after 89.9 (11.1), p < 0.05; ↑; Variety group: before 61.7 (12.3), after 107.6 (10.6), p < 0.05,↑; Potato group: before 53.2 (7.2), after 63.9 (12.0), NS; The carrot (paired t15df = 3.63, P = 0.002) and variety (paired t15df = 3.46, P = 0.003) groups ate significantly more carrots after the 9-d exposure period than before.; ND between group; [underlined: Duration of feeding (min), Mean (SD):]; Carrot group: before 13.0 (1.6), after 18.3 (2.6), NS; Variety group: before 13.8 (1.6), after 16.1 (1.6), NS; Potato group: before 14.1 (2.0), after 15.1 (1.7), NS; ND in duration of feeding before to after intervention among the groups; [underlined: Rate of feeding (g/min), Mean (SD):]; Carrot group: before 4.2 (0.5), after 5.2 (0.6), p < 0.05 ↑; Variety group: before 4.5 (0.8), after 7.0 (0.8), p< 0.05↑; Potato group: before 4.1 (0.5), after 4.2 (0.6), NS; Carrot (paired t15df = 2.23, P = 0.04) and; Variety (paired t15df = 3.52, P = 0.003) groups ate carrots at a faster rate after the exposure period than before.; [underlined: Mother’s rating of infant’s enjoyment of carrots (1, extreme like; 5, extreme dislike), Mean (SD):]; Carrot group: before 1.6 (0.2), after 1.6 (1.8); Variety group: before 1.9 (0.3), after 1.1 (0.1); Potato group: before 1.4 (0.1), after 1.9 (0.3); The only difference in maternal rated liking of carrots was seen in the veg variety group (paired T(15 df)) =2.54, P=0.02); Chicken; [underlined: Intake post-exposure (g) Mean (SD):]; infants in the veg variety group (n=16) consumed more chicken puree than infants in the carrot group (n=16), and potato group (n=16) P<0.05 (ANOVA) (means NR; data presented graphically); [underlined: Duration of feeding (min),]; the rate of feeding (g/min), mothers’ ratings of their infants’ enjoyment (5-point scale): NS (means not reported) [underlined: Impact of fruit exposure:]; Infants who ate fruit daily (n=16) consumed more test carrots than infants who ate no fruit (n=24; P=0.007) (data presented graphically); Model adjustments: baseline response to carrots; Funding source: Grants from NIH and Gerber Companies Foundation; The Gerber Products Company supplied the baby foods
[underlined: Hetherington, 2015]^12^; RCT parallel design, U.K.; Baseline N=40; Analytic N=36; Power analysis: No formal power analysis conducted; authors report that the intervention was sufficiently powered to detect differences between the groups.; Child characteristics:; - Age: 4.83 ± 0.57 mo; - Female: 57%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: 32.20 ± 5.02 y; - Female: 100%; - Race/ethnicity: NR; - Maternal education: 42.9 % below university, 57.1 % university +; Setting: Home (testing in laboratory on d 25, 26, 33, 34 and 35); Objective and primary outcomes: To test the effects (intake and liking of target and unexposed vegetables, primary outcome) of providing vegetables step-by-step in milk and then in cereal during complementary feeding on intake and liking of pure vegetables, and to investigate the acceptability of this strategy among | Target food/Test foods: carrots, green beans, spinach, broccoli puree (generally liked and disliked vegetables; commercially available), parsnip (novel vegetable in post-exposure test); Repeated exposure: Taste; 1/d and 2/d; 35days; 41 exposures (11 per vegetable) Vegetables presented in rotating order 1x/day), caregivers instructed to keep feeding until infant showed 3 clear refusals of feed.; Intervention/control groups:; - Intervention: 12 consecutive days (d 1-12) of exposure to commercial vegetable puree added to milk (1/day; max ~50 g/d), followed by 12 consecutive days (d 13-24) of exposure to vegetable puree added to manufactured rice (2/day; max ~72 g/d), followed by 11 consecutive days of manufactured vegetable purees (1/day; max ~260 g/d), n=18; - Control: 12 consecutive days of exposure to plain milk (1/day; usual quantity), followed by 12 consecutive days of exposure to manufactured plain rice (2/day; max ~77 g), followed by 11 consecutive days of manufactured vegetable purees (1/day; max ~260 g/d), n=18; Outcomes and assessment methods:; - Weighed intake; rate of intake; maternal and unblinded researcher’s perception of infants’ liking of the food (9-point liking scale); - Assessment time: baseline, Day 25/26, Day mothers. 33/34/35, 6-month (acceptance of carrot and green beans) and 18-month follow-up (mother reported liking of green beans and carrot) | [underlined: Vegetable intake (carrot, green bean) at post exposure (g) Mean (SD):]; Intervention vs control: 81.7 (9) vs44.13 (8); [underlined: Intake (laboratory)]; Main effect of group: p < 0.001;; Main effect of time: p = 0.04 ↑;; Vegetable intake from the first, vs second exposure: 55 (6) g vs. 70.8 (8) g; Main effect of vegetable type: p < 0.001;; ↑ Intake of carrot, 83.1 (9) g vs. green beans, 42.7 (5) g; No interactions were significant; [underlined: Rate of eating (laboratory)]; Main effect of group p < 0.01;; Consumption rate of vegetable puree, intervention, 7.5 ± 0.6 g/min vs. control, 4.7 ± 0.55 g/min; Main effect of time, p < 0.001;; ↑ rate of eating from first, 5.2 ± 0.4 g/min to second exposure, 7 ± 0.55 g/min; Main effect of vegetable type: p < 0.01;; ↑ of carrot, 6.7 ± 0.55 g/min vs. green bean, 5.5 ± 0.4 g/min Non-significant interaction effect between time and vegetable; [underlined: Intake (home)]; No main effect of time; Main effect of group: p < 0.001;; ↑ intake of carrot vs. green beans; Main effect of vegetable type: p < 0.001;; ↑ intake of carrot, 76.7 (8.7) g vs. all other vegetables except broccoli, p < 0.001; ↓ intake of Green bean 41 (6) g vs. all other vegetables, p < 0.05; ND intake of Spinach (52.4 (6) g vs. broccoli 67.8 (6) g, p = 0.054; Parsnip intake at d 35 between intervention and control group (laboratory):; 66 (8.6) g vs. 49 (11.7) g; NS; [underlined: Intake, 6 mo follow-up]; Main effect of vegetable: p < 0.05; ↑ intake of carrot vs. green bean.; Main effect of time: significant (NR); Main effect of group: NS, NR; [underlined: Maternal ratings of liking, 6 mo follow-up]; Main effect of group: NS; Main effect of time: NS; Main effect of vegetable: p < 0.001,; ↑ maternal reported liking of carrots, 7.0 (0.3) than green bean, 4.9 (0.34); [underlined: Investigator reported liking, post-intervention]; Main effect of group p < 0.05,; intervention = 6.7 ± 0.3 vs. control = 5.5 ± 0.3; Main effect of time:, p = 0.07; first visit = 5.8 ± 0.3 vs. second visit = 6.4 ± 0.3; Main effect of vegetable p < 0.001; carrot = 7.0 ± 0.3 vs. green bean = 5.1 ± 0.3; [underlined: Investigator reported liking, 6-mo follow-up]; Main effect of group:, p = 0.029; For carrot, intervention, 7.14 (0.53) vs. control, 5.69 (0.49), p = 0.05; For green bean, intervention, 6.14 (0.62) vs. control, 4.56 (0.58), p = 0.07; Main effect of vegetable: p = 0.029; [underlined: Investigator reported liking, 18-mo follow-up:]; analyses not possible due to the low response rate in control group; Model adjustments: NR; Funding source(s): EC Seventh Framework Programme
[underlined: Mennella, 2008]^14^; RCT parallel design, US; Baseline N=88; Analytic N=74; Power analysis: NR; Child characteristics:; - Age: ~6.5 mo (4-9 mo); - Female: 45%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: ~28 y; - Female: NR; - Race/ethnicity: 55.4% Black; 29.7% White; 2.7% Hispanic and 12.2% Other/Mixed Ethnicity; - WIC participation: 100%; Setting: Home (testing in laboratory); Objective and primary outcomes: To test the effects of repeated exposures of single and a variety of fruits and vegetables on acceptance in infants (primary outcome) and the effects of different dietary variety experiences (variety of vegetables within a meal as well as between meals) on infants’ acceptance of the target vegetables (primary outcome) | Target/ Test food: study 1, pear, peach, prune, or apple puree (commercially available); study 2, green bean, squash, spinach, carrot, or pea puree (commercially available); Repeated exposure: Taste; 1/d: 1wk; 8 exposures; Fruit jars contained 71g puree, and vegetable jars contained 110g puree, fed until child rejected the food 3 consecutive times.; Intervention/control groups:; Study 1:; - Pear (P) Group: infants fed commercial pear puree at target meal, 1/d for 8d exposure period, n=20; - Between-Meal Fruit Variety (BM-FV) Group: infants fed commercial peach, prune, or apple puree (not including pear puree), 1 puree/d, variety rotated daily differing from the previous 2 days for 8d exposure period (presented in the order listed), n=19; Study 2:; - Green Bean (GB) Group: Infants fed commercial green bean puree at target meal, n=11; - Between-Meal Vegetable Variety (BM-VV) Group: Infants fed commercial squash, spinach, carrot, or pea puree at target meal (not including green bean puree). Infant was fed 1 puree/d and the type of vegetable differed from the day before (green and orange variety alternated daily in the order listed), n=12; - Between-Meal and Within-Meal Vegetable Variety (BM-WM-VV) Group: Infants fed 2 commercial vegetable purees during each day of the exposure period: 1 green vegetable (spinach or peas) & 1 orange vegetable (squash or carrots); vegetable pair varied daily and included 1 of the purees offered the previous day; infants fed 1-2 spoonful of 1 puree then switched to the other puree, n=12; Outcomes and assessment methods; - Weighed intake; duration of feeding; rate of feeding (videotapes by blind observers); maternal rating of infant’s liking of test food (in lab); - Assessment time: pre-exposure test (day 1 and 2), post-exposure test (day 11 and 12) | Study 1; [underlined: Intake during exposure (g; pear, peaches, prunes, and] apples): 49.2 (3.2), 52.8 (3.8), 51.8 (4.1), 56.0 (3.8).; Calorie intake between groups, BM versus Pear group: ↑ (p<0.0001).; [underlined: Pear, pre vs. post]; Intake (kcal):; P group, 44.7 (6.5) vs. 55.8 (6.4), p=0.04 ↑;; BM variety group, 52.6 (8.1) vs. 66.8 (9.5), p=0.02 ↑; Length of feed (min): no change in either group;; Rate of feed (g/min): no change in either group;; Mothers’ ratings of the infants’ enjoyment: no change in either group; [underlined: Green beans, pre vs. post]; Intake (kcal) of novel food: no change before to after exposure for either group;; Length of feed (min): no change in either group;; Rate of feed (g/min):; P-group, 3.7 (0.4) vs. 4.9 (0.7), p<0.05 ↑;; BM-V group, 5.2 (1.1) vs. 6.3 (1.1), p<0.05 ↑;; Mothers’ ratings of the infants’ enjoyment: no change in either group; Study 2; Calorie intake in between groups, green bean, BM and BM-WM: No difference; [underlined: Intake of green beans (kcal), pre vs. post]; GB group, no change;; BM-V group, no change;; BM-WM-VV 12.2 (2.9) vs. 27.2 (4.5), p=0.002 ↑;; Length of feed, green beans, (min): no change for any group;; [underlined: Rate of feed, green beans(g/min):]; GB group, 4.9 (0.8) vs. 7.2 (1.0), p<0.05↑;; BM-WM 3.5 (0.6) vs. 5.9 (0.6), p<0.05↑;; BM-V group, no change;; Mothers’ ratings of the infants’ enjoyment: no change for any group;; [underlined: Intake of carrot (kcal), pre vs. post:]; BM-WM-VV, 9.0 (1.9) vs. 16.6 (3.1), p=0.03 ↑;; GB or BM-V groups, no change; [underlined: Intake of spinach (kcal) pre vs. post:]; BM-WM-VV 8.7 (2.0) vs. 19.9 (4.2), p=0.03 ↑; G; B or BM-V groups, no change; [underlined: Length of feed, spinach (min):]; No change for any group;; [underlined: Rate of feed, spinach (g/min):]; BM-V, 4.3 (0.5) vs. 5.6 (0.5), p<0.05 ↑;; BM-WM-VV, 3.8 (0.6) vs. 6.1 (0.8), p<0.05↑;; GB-group, no change;; [underlined: Mothers’ ratings of the infants’ enjoyment of carrots:]; No change before for any group;; [underlined: Mothers’ ratings of the infants’ enjoyment of spinach:]; No change for any group;; Model adjustments: None; Funding source(s): NIH Grant HD37119; Gerber Products Company supplied the baby foods
Paul, 2011^16^; RCT parallel 2 × 2 design, US; Baseline N=160; Analytic N= 110; Power analysis: NR; Child characteristics:; - Age: NR (recruited mother-newborn dyads; infants assessed through age 1 y); - Female: 56%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: 27.1 y; - Female: 100%; - Race/ethnicity: 91% White, 6% Black, 1% Native American, 6% Hispanic ethnicity; - Education: 65% college degree, 21% some college, 15% High school or less; - Marital status: 90% married; - Annual household income: 23% >100 K, 42% 50-99K, 18% 25-49K, 10% <25K; Setting: Home (container weighed in lab); Study objective and primary outcomes: To test the independent and combined effects of 2 behavioral interventions – soothe/sleep and introduction to solids, delivered to parents, designed to promote healthy infant growth in the first year. Primary outcome was weight-for-length percentile at age 1 year. Amount of target vegetable consumed (g/d) as secondary outcome. | Target food/test foods: green beans, peas, squash, carrots (commercial); Repeated exposure: Taste; 1/d: 4wk; 24 exposures; For 4 successive weeks, 1 of 4 pureed vegetables (amount, NR) fed to child each week for 6 consecutive days in the following order were fed by parent: green beans, peas, squash, carrots. Nurse provided education in accordance to intervention group. Parents fed until child refused 3 consecutive times.; Intervention/control groups:; - Both interventions (Soothe/Sleep intervention + Introduction of Solids interventions) (n=22); - Control + Introduction of Solids interventions (n=29); - Soothe/Sleep intervention + control (n=29); - Control + control: standard handout from the American Academy of Pediatrics on the introduction of solid foods, (n=30); Outcomes and assessment methods:; - Weighed intake; - Assessment timing: Day 1 and 6 of exposure series for 4 target vegetables | [underlined: Vegetable intake (g/d) change from day 1 to 6, both interventions and in the introduction to solids + control group:]; Green beans: ↑ P = 0.001; Peas: ↑ P = 0.02; Squash: ↑ P = 0.04; Carrots: No change, NS; Model adjustments: None; Funding source(s): NIDDK, NIH, GCRC Construction Grant, the Penn State Children, Youth and Families Consortium and The Children’s Miracle Network. Infant food jars were donated by Gerber.
[underlined: Remy, 2013]^17^; RCT parallel design, France; Baseline N=100; Analytic N=95; Power Analysis: N=24 participants required in each group to observe significant differences in intake; between pre- and postmeasurements.; Child characteristics:; - Age: ~6.4 mo; - Female: 40%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - SES: NR; - Race/ethnicity: NR; Setting: Home; Objective and primary outcomes: To investigate and compare the efficacy of the 3 mechanisms, repeat exposure, flavor-flavor learning and flavor-nutrient learning, at increasing the acceptance (intake and liking) of a vegetable at the beginning of complementary feeding; 2) to measure the stability of the learning in the short and middle term; and 3) to examine the influence of infants feeding history on the acceptance of the vegetable. | Target food/ Test food: Artichoke (pureed – basic, sweetened and energy dense; lab-made); Test: artichoke and carrot; Repeated exposure: Taste; 1/d; 2-3/wk; 10 exposures; Child fed puree (100g jar) until 3 consecutive refusals; Intervention/control groups:; - Repeated exposure (RE): infants fed basic artichoke puree (lab-made), n=32; - Flavor-flavor learning (FFL): infants fed sweetened artichoke puree (lab-made), n=31; - Flavor-nutrient learning (FNL): infants fed energy-dense artichoke puree (lab-made), n=32; Control food: carrot puree (commercially available); No other vegetables offered at meal; Outcomes and assessment methods:; - Weighed intake; parent rated liking (scale of 1-9); - Assessment timing: pre-and post-exposure, 3-mo follow-up, 6-mo follow-up; 2-wk follow-up (artichoke acceptance only) | [underlined: Basic artichoke puree intake (g), Mean (SD):]; ↑ intake after the exposure period in RE: 56 (14), p<0.001; Follow-up (2 wk, 3 mo, 6 mo) change from post-exposure: no significant changes across follow-up times for any groups; [underlined: Basic artichoke puree liking:]; ↑ in liking after the exposure period in the RE group (1.3 (0.05), p<0.01); 2 wk follow-up from post-exposure: no change or difference among groups;; 3 mo follow-up from post-exposure: ↓in liking for the FFL group (FFL −1.0 (0.4), p<0.01); 6 mo follow-up from post-exposure: ↓ in liking in all groups at 6mo follow-up compared to post-exposure (RE −2.0 (0.5),p<0.001; FFL −1.7 (0.5), p<0.001; FNL −1.5 (0.5), p<0.05), No difference in liking at 6 mo follow-up in RE group; [underlined: Intake post exposure (g), carrot vs. artichoke, Mean:]; No difference in RE group (159 g vs. 145 g).; ↑ carrot intake vs artichoke in the FFL and FNL groups (FFL: 178 vs. 147, p=0.007; FNL: 166 vs. 107, p=0.0001); [underlined: Liking post-exposure, carrot vs. artichoke, Mean:]; No difference in RE (7.4 vs. 7.3) and FFL (7.3 vs. 7.2) groups; Model adjustments: Model 1: age at complementary feeding, age at the beginning of the study, number of days between the start of complementary feeding and the beginning of the study, duration of exclusive breastfeeding, Z-score of BMI, and infants’ weight at each period of the study, number of vegetables eaten before the study; Funding source(s): NR
[underlined: Sullivan, 1994]^18^; RCT within-subjects design, US; Baseline N=36; Analytic N=36; Power calculation: NR; Child characteristics:; - Age: ~22 wk (17-27 wk); - Female: 58.3%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: 100%; - Race and/or ethnicity: NR; - SEP: NR; Setting: Home; Objective and primary outcomes: To examine the effects of dietary experience and milk feeding regimen on acceptance of the first vegetable by 4- to 6- month-old infants. Primary outcomes: target vegetable intake and liking. | Target food/ Test foods: green beans and peas (salted and unsalted; commercially available); chicken or tofu (test food); Repeated exposure: Taste; 1/d; 10d; 10 exposures; Either version of salted or unsalted vegetable (green beans or peas) offered from a jar (blinded for salted vs. unsalted). Target food offered when infants were calm and alert state until infant refused 3 consecutive offerings and prior to consumption of any other foods or milk.; Intervention/control groups:; - Green beans (unsalted): 71g pureed.; - Green beans (salted; 0.3gNaCl/100g): 71g pureed.; - Peas (unsalted): 71g pureed; - Peas (salted; 0.3gNaCl/100g): 71g pureed.; - Control foods: Pureed chicken or tofu (1 infant only); Outcome and assessment methods:; - Weighed intake; infant’s behavioral responses (on a scale of 1-5) assessed by 2 mothers and research assistance as food presented in counterbalanced order; - Assessment timing: pre-exposure (day 1, 2, and 3) followed by 1d delay, post-exposure (day 15, 16 and 17) followed by 7d delay, post delay exposure (day 25 and 26) | [underlined: Intake of exposed vegetable (g), Mean:]; ↑ salted groups (28 to 63); unsalted groups (36 to 58) p-time<0.01, p-vegetable<0.05).; No change in intake from post-exposure to post-delay.; Main effect of time: P<0.001; Effect of time, vegetable, and version (salted and unsalted): No interaction; Effect of sex: No main effect and no interaction of sex with other factors.; ↑ intake of peas versus green beans (salted and unsalted), P<0.05; [underlined: Intake of unexposed vegetable (salted or unsalted) (g), Mean:] ↑ from pre- to post-exposure, p=0.05, with no impact of exposure to salt.; ↑ from pre-exposure to post-delay, p=0.05, with no impact of exposure to salt.; [underlined: Mean intake of novel food (chicken or tofu):]; No change from pre- to post-exposure to post delay, NR; [underlined: Liking of exposed and unexposed vegetable (salted and unsalted:]; Exposed: ↑ from pre- to post-exposure p<0.001; Unexposed: ↑ from pre- to post-exposure, p<0.01; [underlined: By feeding regimen (Bf vs. FF)]; Main effect of time by feeding regimen: P<0.05; Main effect of feeding regimen: P<0.01; Overall intake of exposed veg; ↑, P<0.01; Intake over time; ↑ BF: P<0.001 vs. FF:P<0.05; Control food; No difference, NR; Intake of exposed veg during exposure; ↑ 50g vs. 33g, P<0.01; Intake of exposed veg post exposure: ↑, P<0.05; Model adjustments: Model 1: none; Model 2: sex; Model 3: BF or FF outside of intervention.; Funding source(s): Gerber Products Company, NIH
Birch, 1998^19^; NRCT, US; Baseline N: NR; Analytic N=39; Power calculation: NR; Child characteristics:; - Age: ~24 wk (16-31 wk); - Female: 54%; Caregiver characteristics:; - Age: Mothers: 31 (20-44) y; Fathers: 32 (22-34) y; - Race/ethnicity: NR; - Education, average: 15 y; (mothers and fathers); - SEP (mothers): Did not work outside the home: 44%, <30 hours/wk: 23%, Full-time jobs: 31%; Setting: Home; Objective and primary outcomes: To investigate how much experience with a new food is sufficient to increase infants’ intake of that new food; and whether experience with 1 food is sufficient to increase intake of other new foods, varying in their similarity to the target food. in a sample of 4- to 7-month-old infants. Primary outcome is intake. | Target foods/ Test: Bananas and peas (commercially available); Repeated exposure: Taste; 1/d for 10 d, 10 exposures; 226 g of food was offered by the mother and fed until 3 consecutive refusals. Bananas group: Same food but different brand; Similar foods: peaches/pears; Different foods: peas; Home-prepared bananas; Peas group: Same food but a different brand; Similar foods: carrots/corn; Different foods: beef; Home-prepared peas; Intervention/control:; - Gerber bananas (n=9); - Growing Healthy bananas (n=8); - Gerber peas (n=11); - Growing Healthy peas (n=11); Outcomes and assessment methods:; - Weighed intake; - Assessment timing: Pre-test days 1-5, posttest days 11-16 | [underlined: Intake, Bananas vs peas group (between-group)]; Target food (both groups): NS (data NR); Same food from different brand: NS (data NR); Similar foods: NS (data NR); Different foods: NS (data NR); [underlined: Intake, Pre-exposure vs post-exposure (within-group)]; Target food: (data NR), p<0.01 ↑; Bananas/peas from different brand: NS (data NR); Peaches/pears (bananas group) or carrots/corn (peas group): p<0.01↑; Peas (bananas group) or bananas (peas group): 33 g vs 35 g, p>0.05; Home-prepared bananas (bananas group) or peas (peas group): No change; Model adjustments: brand, infant feeding regiment, infant gender; Funding source(s): Growing Healthy
[underlined: Maier, 2007]^20^; NRCT, Germany; Baseline N=75; Analytic N=49; Power calculation: NR; Child characteristics:; - Age: 7.0 ± 0.9 mo; - Female: 49%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: ~32y; - Female: 100%; - Race and/or ethnicity: NR; - Education: 21% Primary; 57% Secondary; 21% Tertiary; Setting: Home; Objective and primary outcomes: To assess the proportion of mothers reporting that during the first mo of vegetable feeding their infant disliked or refused a vegetable purée to the extent that they would not normally offer it again; to measure the change in acceptance of 1 initially disliked vegetable across repeated exposures vs. the change in acceptance of an initially well-liked, control vegetable and (3) to examine the possible influences of breastfeeding, experience with variety and mother’s neophobia, variety seeking and anxiety on the frequency of vegetable dislike and on acceptance of a disliked vegetable during repeated exposure. | Target food/Test food: disliked vegetable chosen by mother (artichoke, peas, cauliflower, green beans, pumpkin, spinach, zucchini/tomato), prepared purées. Test food: disliked vegetable and carrot (liked vegetable); Commercially available; Repeated exposure: Taste; 1/d; 16d; 8 exposures; Mothers offered disliked vegetable and liked vegetable on alternating days for 16 days. Mothers provided with 3 jars (130g each) of appropriate puree and instructed to offer until infant refused 3 consecutive offerings or until she considered child had eaten enough. Mothers rated infant liking at the end of each meal and brought used jars back to lab for measurement.; Intervention/control groups:; Control food: Carrots (liked vegetable); Outcomes and assessment methods:; - Weighed intake; maternal ratings of child vegetable liking (on a scale of 1-9); - Assessment timing: post-meal; 9 mo post-delay exposure (infants aged 15-19 mo) | [underlined: Intake of disliked and liked vegetable during intervention (g), Mean ± SD:]; Disliked vegetable: ↑ over 8 exposure days; 39 ± 29 vs. 174 ±54 (r=0.99; p<0.0001); Liked vegetable: ↑ over 8 exposure days; 164 ± 73 vs.186 ±68 (p=0.03); [underlined: Liking of disliked and liked vegetable during intervention, Mean ± SD:]; Disliked vegetable: ↑ over 8 exposure days; 3.1 ± 1.5 vs. 8.0 ± 1.1 (r=0.99); Liked vegetable: ↑ over 8 exposure days; 7.3 ± 1.3 vs. 7.6 ± 1.3; [underlined: Exposure and individual intake and liking patterns during intervention:]; At 3 exposures to disliked vegetable, 6% (n=3) were eating as much of the initially disliked vegetable as the liked vegetable; At 8 exposures to the disliked vegetable, 71% (n=35) were eating as much of the initially disliked vegetable as the liked vegetable; [underlined: Maternal ratings of vegetable liking at 9 mo follow-up]; 83% infants rated as eating and liking liked vegetable (carrot); 8% infants rated as eating and not liking liked vegetable (carrot); 63% infants rated as eating and liking disliked vegetable; 12.5% infants rated as eating and not liking disliked vegetable; 10% infants rated as disliking/refusing disliked vegetable; Model adjustments: child age; Funding source(s): Nestle Nutrition, Vevey, Switzerland
[underlined: Blomkvist, 2021]^4^; Cluster RCT, Norway; Baseline N=267 (n=46 clusters); Analytic N=144; Power calculations: sample size calculated based on food neophobia scores, power of 80%and type 1 error of 5% adjusted for cluster variation suggested 58 per group; Child characteristics:; - Age: 16.7 (3.0) mo; - Female: 47.6%; - Race/ethnicity: 100% born in Norway; Caregiver characteristics:; - Age: 30.9 (5.4) y; - Female: 88.7%; - Education: 64% mothers with university degree/ 42% fathers with university degree; - SEP: marital status (parents living together): 94.3%; Setting: kindergartens; Study objective and primary outcomes: to assess the effect of a web-based intervention that involved serving vegetables with lunch meal with the purpose to promote a healthy and varied diet amongst 1-year-old children. Child intake of intervention vegetables and all vegetables combined, and level of child food neophobia post-intervention | Target/Test food: spinach, celeriac, fennel (novel); Repeated exposure: Non-taste & Taste; 2x/wk; 3 wks; at least 6 exposures; Intervention vegetables were served with warm lunch meals on alternating days at least 2x per week for 3 weeks. There was a 1-week washout break between vegetables.; Intervention/control:; - Diet group (TE): 3-month intervention; 1 intervention vegetable introduced per month served with lunch (spinach/celeriac/fennel), n=42; - Diet+Sapere group (TE & NTE): 3-month intervention; 1 intervention vegetable introduced per month served with lunch (spinach/celeriac/fennel), Additional sensory lessons with vegetable of the month (9 additional exposures to intervention vegetable of the month), n=63; - Control group: usual meal practices, n=39; Outcomes and assessment methods:; - Child intake of intervention vegetables and all vegetables combined (digitally distributed food frequency questionnaire completed by parent, response options re-coded into times consumed per week); - Assessment timing: baseline, post-intervention at 1 month | [underlined: Intake of total vegetable (times/wk) at baseline and post-intervention, Median (IQR)]; Total vegetable: (control/diet/diet+Sapere); Baseline: 18.7 (11.2-23.4), 17.6 (12.4-26.8), 20.5(13.3-28.5); Post-intervention: 19.6 (12.8-24.9), 17.1 (11.4-27.3), 18.2 (11.1-26.6); [underlined: Intake of intervention vegetables (times/wk) at baseline and post-intervention, Median (IQR)]; Intervention vegetables: (control/diet/diet+Sapere); Baseline: 0.0 (0.0-0.3), 0.1 (0.0-0.7), 0.1 (0.0-0.5); Post-intervention: 0.1 (0.0-0.2), 0.3 (0.0-1,1), 0.1 (0.0-0.5); [underlined: Effect of intervention on frequency of total vegetable intake]; Group: IRR (95% CI), P-value; Diet: 1.20 (95% CI:0.98-1.47), P=0.07; Diet+Sapere: 1.14 (95% CI:0.93-1.39), P=0.22; [underlined: Effect of intervention on frequency of intervention vegetables intake] Group: IRR (95% CI), P-value; Diet: 1.80 (95% CI:0.78-4.13), P=0.17; Diet+Sapere: 2.63 (95% CI:1.14-6.05), P=0.02; [underlined: Effect of intervention on probability of having total vegetable intake in accordance with national recommendations (≥17.5/wk)]; Group: RR (95% CI), P-value; Diet: 1.11 (95% CI:0.83-1.50), P=0.46; Diet+Sapere: 1.03 (95% CI:0.71-1.48), P=0.88; [underlined: Effect of intervention on probability of having intervention vegetables intake at least 1x/week]; Group: RR (95% CI), P-value; Diet: 3.08 (95% CI:0.84-11.3), P=0.091; Diet+Sapere: 2.85 (95% CI:0.77-10.46), P=0.12; Model adjustment: adjusted for baseline value of total veg. + maternal and paternal education, standard errors were corrected for cluster design with robust estimator; Funding source: Norwegian Women’s Public Health Association, University of Agder, the Teacher’s Education Unit at the University of Agder, Hospital of Southern Norway
[underlined: Dazeley, 2015]^7^; Cluster RCT, U.K.; Baseline N= 121; Analytic N= 92 (n=12 clusters); Power analysis: NR; Child characteristics:; - Age: ~2y; - Female: NR; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: NR; Setting: Nursery schools; Study objective and primary outcomes: to test the effects of a holistic, sense-based approach to food familiarization. Primary outcome: willingness to taste foods | Target/test food: Set A: sweet potato, green pepper, rhubarb, dried figs. Set B: butternut squash, broad beans, dried prunes, pomegranates. Unfamiliar foods; Repeated exposure: Non-taste; 4d/wk; 4 wks; max 16 exposures; Children received 5-10 minutes per day of food-related activities focused on 1 of the senses (randomly determined). Tasting of foods was discouraged. Half the groups completed activities with Set A foods, half with Set B foods; Intervention/control:; - Experimental group A: 4-week intervention. Completed non-taste exposure (NTE) activities with Set A foods, n=24; - Experimental group B: 4-week intervention. Completed NTE activities with Set B foods, n=31; - Control: no exposure activities, n=37; Outcomes and assessment methods:; - Willingness to consume Set A and Set B foods offered by nursery staff in counterbalanced order: researcher recorded foods participants touched and tasted (mean number of Set A and Set B food); - Assessment timing: 1 week post intervention | [underlined: Number of foods in each set tasted by group, mean (SD)]; Experimental group A:; No differences in mean numbers of foods tasted (p>0.05); Experimental group B:; Vegetable: Set A 0.57 (0.78) vs. Set B 0.78 (0.80), p<0.05 ↑; No other differences in mean numbers of foods tasted (p>0.05); Experimental groups combined:; Vegetable: Exposed 0.75(0.78) vs. Non-exposed 0.57(0.74).; P<0.05 ↑; No other differences in mean numbers of foods tasted (p>0.05); Model adjustments: none; Funding source(s): Innovate U.K.
[underlined: Heath, 2014]^11^; RCT parallel design, U.K.; Baseline N=68; Analytic N=57; Power analysis: NR; Child characteristics:; - Age: 22mo 9d (range: 20mo 26d to 24mo 0d); - Female: 46.7%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: 95%; - Race/ethnicity: 88% white; - SEP: 78% at least 1 parent educated to graduate level; Setting: Home (laboratory taste test); Study objective and primary outcomes: To investigate how a food’s initial status impacts on a picture books’ effectiveness as a means of increasing children’s willingness to taste target foods. Primary outcome: Willingness to taste target food. (Experiment 2) | Target food/ Test Foods: liked, disliked, or unfamiliar vegetable (determined by parent report); Repeated exposure: Non-taste; ~5 min/d for 2 weeks; average 14.9 (SD=9.9) exposures; Children looked at picture book about target vegetable with parents for 2 weeks. At post-intervention children were offered 3 small pieces of target and control vegetables. Vegetables were counterbalanced.; Intervention/control:; - Liked: vegetable book containing initially liked vegetable, n=19; - Disliked: vegetable book containing initially disliked vegetable, n=19; - Unfamiliar: vegetable book containing initially unfamiliar vegetable, n=19; - Control (nonexposed) food was selected by parent within the same category; Outcomes and assessment methods:; - Willingness to taste: whether food was tasted, order in which food was tasted; Intake: amount of food consumed assessed as the proportion of the portion provided on a 5-point scale; - Assessment timing: post-intervention | [underlined: Willingness to taste, whether target food was tasted]; Exposed vs nonexposed: No difference, χ2 (1) = 3.29, p = 0.07 (data NR); No main effect of exposure, G2 (1)=2.04, p=0.15; No main effect of group (liked, disliked, unfamiliar), G2 (2) = 2.04, p= 0.36,; No interaction effect exposure x group, G2 (7) = 4.14, p = 0.76.; [underlined: Willingness to taste, order food was tasted, tasted first]; ND in whether children tasted target food vs. control food first, n=49, p=0.15; ND between group (liked, disliked, unfamiliar) on whether target food was tasted first, χ2 (2)=0.02, p=0.66.; [underlined: Intake, proportion of portion provided rated on a 5-point scale]; Target vs control vegetable; Total sample: Z = −2.4, p = 0.016 ↑; Liked group: ND: Z = −0.77, p = 0.44; Disliked group: ND Z = −0.95; p = 0.34; Unfamiliar group: Z = −2.5, p = 0.011 ↑; Model adjustments: none; Funding source(s): NR
[underlined: Houston-Price, 2019]^13^ (same population as Owen, 2018); RCT parallel design, U.K.; Baseline N=127; Analytic N=100; Power analysis: NR; Child characteristics:; - Age: 21.6 (1.6) mo (18-24 mo); - Female: ~50%; - Race/ethnicity (White British): ~83%; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: household income (% £50 k+ pa): ~49%; educational status (with degree): ~60%; marital status (married): ~77 %; Setting: Home; Study objective and primary outcomes: to examine typical time course of acceptance/rejection of disliked or unfamiliar foods when young children are offered repeated exposures to these at home; to examine if prior visual familiarization to a food support parents in introducing it. Primary outcomes child’s liking and consumption. | Target food: single fruit and vegetable chosen by parent’s perception of child’s dislike (disliked food/ food refused to be eaten/unfamiliar food); Repeated exposure: Taste & non-taste; 1/day; 2wk; 15 exposures (mean 13, range 5-15); Parent provided repeated non-taste and taste exposure to target fruit and vegetable, child-sized portion of each food (defined as the amount that would fit into the palm of their child’s hand), prepared in manner the child likes, but the same way each day.; Intervention/control:; - Fruit book group: 2 wk visualization phase; look at picture book about child’s target fruit photo story for ~5 minutes daily, followed by repeated taste exposure to 2 target foods (a fruit and a vegetable), n=32; - Vegetable book group: 2 wk visualization phase; look at picture book about child’s target vegetable photo story for ~5 minutes daily, followed by taste exposure to 2 target foods (a fruit and a vegetable) n=34; - Control group: No visualization exposure, taste exposure to 2 foods, n=39; Outcomes and assessment methods:; - Outcomes: Food liking via parent report (5-point scale); mean intake (child-sized portion on a scale from 0 to 4); mean proportion of offers tasted (number of tastes/number of offered); - Assessment timing: Baseline and 3-month (15±2wk) follow-up | [underlined: Main effect of time, within-subject difference baseline to 15 weeks]; Fruits: Main effect of time; Proportion of offers tasted, χ2 (2) = 0.74, p = 0.69,; Mean intake per offer, χ2 (2) = 2.49, p = 0.29,; Mean liking, χ2 (2) = 3.05, p = 0.22; Vegetables:; Proportion of offers tasted, χ2 (2) = 4.58, p = 0.10,; Mean intake per offer, χ2 (2) = 2.38, p = 0.30,; Mean liking, χ2 (2) = 5.61, p = 0.061; [underlined: Early (d1-5) compared to middle (d 6-10) and later (d 11-15) days of exposure, within-subject difference in diary measures (data presented graphically)]; Fruits:; Proportion of offers tasted, No difference (P>0.05); Mean intake per offer, No difference (P>0.05); Mean liking, Z = 2.06, p = 0.039 ↑ (early to middle days of exposure); Vegetables:; Proportion of offers tasted, No difference (P>0.5); Mean intake per offer, No difference (P>0.5); Mean liking, No difference (P>0.5); [underlined: Early (d1-5) to latter (d 11-15) exposure, within-subject difference]; Vegetables:; Mean liking, Z = 2.21, p = 0.027 ↑; [underlined: Middle (d6-10) to later (d 11-15) exposure, within-subject difference]; Fruits:; Proportion of offers tasted, No difference (P>0.5); Mean intake per offer, No difference (P>0.5); Mean liking, No difference, (P>0.5); Vegetables:; Proportions of offers tasted, Z = 1.97, p = 0.049 ↑; Mean intake per offer, Z = 2.26, p = 0.024 ↑; Mean liking, No difference (P>0.5); [underlined: Prior visualization and repeated taste exposure, Between group difference baseline to 15 weeks]; [underlined: Fruit: fruit book group versus no visualization (vegetable and control group):]; Proportion of offers tasted, U = 1008.00, Z = 0.59, p = 0.55,; Mean intake per offer, U = 1017.00, Z = 0.53, p = 0.60,; Mean liking, U = 742.50, Z = −0.88, p = 0.38; No differences between groups during any individual phase of exposure (all ps > 0.05).; [underlined: Vegetable: Vegetable book group versus no visualization (fruit book and control group):]; Proportion of offers tasted, U = 923.00, Z = 1.45, p = 0.15; Mean intake per offer, U = 890.00, Z = 1.70, p = 0.09; Mean liking, U=516.00, Z=2.65, p=0.008; Number of exposures provided, U = 930.00, Z = 1.42, p = 0.16; Middle days of exposure (d 6-10); Proportion of offers tasted, U = 744.00, Z = −2.52, p = 0.012 ↑; Early days (d 1-5); Mean liking of the vegetable, U = 431.00, Z = 2.29, p = 0.022↑; Later days of exposure (d 11-15); Mean liking of vegetables, U = 173.00, Z = −2.47, p = 0.013↑; No other differences between groups during any individual phase of exposure (all ps > 0.05).; [underlined: *Preliminary analysis during taste exposure: Child ethnic origin predicted mean liking for vegetables.] White British children reported to like target vegetable less than children in other ethnic groups (small sample in the latter group, n=17), U=292, Z=2.82, p=0.005; Model adjustments: None; Funding source(s): NR
[underlined: Owen, 2018]^15^ (Same population as Houston-Price, 2019); RCT parallel design, U.K.; Baseline N=127; Analytic N=100; Power analysis: NR; Child characteristics:; - Age (Mean): 21.6 (1.6) mo (18-24); - Female: ~49%; - Ethnicity (White British): ~83.5%; Caregiver characteristics:; - Age (Mean): NR; - Female: NR; - Race/ethnicity: NR; - Household income (% £50 k+ pa): ~55.6%; - Educational status: 55.4% with degree; - Marital status (married): ~73%; Setting: Home; Study objective and primary outcomes: To explore whether looking at picture books before providing foods to taste improved the outcomes of a home-delivered taste exposure regime; whether parents’ attempts to introduce fruit and vegetables through repeated taste exposure were helped by prior visual familiarization to foods – specifically, a period spent looking at picture books about foods. Primary outcomes: child’s liking and consumption. | Target food: Single fruit and vegetable chosen by parent’s perception of child’s dislike; Repeated exposure: Non-taste & Taste; 1/day; 2wk; 15 exposures; Parent provided repeated exposure to target fruit and vegetable (provided), child-sized portion of each food (defined as the amount that would fit into the palm of their child’s hand), prepared in manner the child likes, but the same way each day.; Intervention/control:; - Fruit book group: 2 wk visualization phase; look at picture book about child’s target fruit photo story for 5 minutes daily for 14d, followed by exposure to 2 target foods (a fruit and a vegetable) daily for 15d, n=42; - Vegetable book group: 2 wk visualization phase; look at picture book about child’s target vegetable photo story for a few minutes every day. Followed by exposure to 2 target foods (a fruit and a vegetable) daily for 15d, n=46; - Control group: No visual phase; Exposure to 2 target foods daily for 15d, n=39; Outcomes and assessment methods:; - Child’s liking of target food- Fruit and Vegetable Familiarity & Liking Questionnaire (6-point scale); Child’s consumption of target food and total fruit and vegetable intake – Child Food Frequency Questionnaire (CFFQ), mean proportion of offers tasted (number of tastes/number offered); - Assessment timing: baseline, post-intervention (1wk) and 3-month follow-up | [underlined: Intake of target food (portions/d) at baseline, post-intervention and follow-up, Mean (SD)]; Fruit intake: Fruit book, Vegetable book, Control group, All children; Baseline: 0.03(.09), 0.07(0.17), 0.20(0.59), 0.09 (0.35); Post-intervention: 0.46 (0.50), 0.43(0.53), 0.36(0.41), 0.42(0.48); Follow-up: 0.11 (0.23), 0.15(0.16), 0.12(0.21), 0.13(0.20); [underlined: Effect of visual familiarization (non-taste exposure) on intake of target fruit]; Main effects of time, NS; p = 0.34, ηp2 = 0.01; Group, NS; p = 0.43, ηp2 = 0.02; Group × Time interaction, NS; p = 0.26, ηp2 = 0.04.; No main effects for time, group or group × time interaction; [underlined: Vegetable intake: Fruit book, Vegetable book, Control group, All children (g), Mean SD]; Baseline: 0.06(0.13), 0.15 (0.46), 0.14(0.38), 0.11 (0.35); Post-intervention: 0.35 (0.37), 0.41(0.43), 0.30(0.35), 0.35(0.38); Follow-up: 0.15 (0.21), 0.27(0.22), 0.11(0.16), 0.18(0.21); [underlined: Effect of visual familiarization (non-taste exposure) on intake of target vegetable]; Main effect of Time, p = .004, ηp2 = 0.11; Main effect of Group, F(2,75) = 1.13, NS; p = 0.33, ηp2 = 0.03,; Group × Time interaction, p = .02, ηp2 = 0.10; Consumption of target vegetable (group differences); Vegetable Book: p = .001, ηp2 = 0.35; Fruit Book: p = .08, ηp2 = 0.14; Control: p = .89, ηp2 = 0.001; Vegetable Book group vs Control group: t (75) = 2.79, p = 0.007 ↑; Vegetable book group vs Fruit book group: t (75) = 1.95, p = 0.055 ↑; [underlined: Liking of target food (portions/d) at baseline, post-intervention and follow-up, Mean (SD)]; Fruit liking: Fruit book, Vegetable book, Control group, All children; Baseline: 1.75(0.65), 1.93(0.91), 2.04(0.79), 1.91(0.79); Post-intervention: 3.25 (1.40), 3.27(1.39), 3.36(1.28), 3.29(1.35); Follow-up: 3.11 (1.49), 3.41(1.40), 3.16(1.28), 3.28(1.35); [underlined: Effect of visual familiarization (non-taste exposure) on liking target fruit]; Main effect of Time, p < .001, ηp2 = 0.44; Baseline to post-intervention: p < .001, ηp2 = 0.46 ↑; Baseline to follow-up: p < 0.001, ηp2 = 0.47 ↑; Post intervention to follow-up: No change F(1, 62) = 0.29, NS; p = 0.59, ηp2 = 0.005; Main effect of Group: NS; p = 0.73, ηp2 = 0.01; Group × Time interaction, NS; p = 0.80, ηp2 = 0.01.; [underlined: Vegetable liking: Fruit book, Vegetable book, Control group, All children, Mean (SD)]; Baseline: 2.00 (0.71), 1.74 (0.73), 1.83 (0.66), 1.85 (0.70); Post-intervention: 2.45 (1.15), 3.65(1.05), 2.41(1.12), 2.85(1.24); Follow-up: 2.50 (1.15), 3.30(1.26), 2.63(1.21), 2.87(1.30); [underlined: Effect of visual familiarization (non-taste exposure) on liking of target vegetable]; Main effect of Time, p < 0.001, ηp2 = 0.39; Main effect of Group, p = 0.047, ηp2 = 0.09; Vegetable Book: p < 0.001, ηp2 = 0.56;; Fruit Book: p = 0.005, ηp2 = 0.25;; Control: p = 0.001, ηp2 = 0.31.; Group × Time interaction, p = 0.004, ηp2 = 0.12; Vegetable Book vs. Controls: t (87) = 4.01, p < 0.001;; Vegetable Book vs. Fruit Book: t (87) = 4.47, p < 0.001); Vegetable Book vs. Controls at follow-up: t (64) = 2.31, p = 0.024;; Vegetable Book vs. Fruit Book at follow-up: t (64) = 2.43, p = 0.018); [underlined: Total fruit intake]; Main effect of Time p = 0.008, ηp2 = 0.07; intake from baseline to follow-up, p = 0.003, ηp2 = 0.12 ↓.; Group effect F(2,66) = 0.49, NS; p = 0.61, ηp2 = 0.02; Group × Time interaction, F(4,132) = 0.98, NS; p = 0.42, ηp2 = 0.03.; [underlined: Total vegetable intake]; Main effect of time: NS p = 0.073, ηp2 = 0.04.; Group effect: NS; p = 0.69, ηp2 = 0.01; Group × Time interaction: NS; p = 0.72, ηp2 = 0.01; [underlined: Predictors of liking of target vegetable at baseline, post-intervention, and follow-up]; The number of times the target vegetable was offered (NS ;p> 0.05); The number of times children tasted the vegetable and liking both post-intervention, r(85) = 0.57, p < 0.001 and at follow-up, r(64) = 0.50, p < 0.001; Post-intervention:; Fruit Book: r(28) = 0.61, p < 0.001; Vegetable Book: r(29) = 0.73, p < 0.001; Control: r (28) = 0.38, p < 0.048); Follow-up; Fruit Book: r(19) = 0.49, p = 0.031; Vegetable Book: r(22) = 0.66, p = 0.001; Control: r(23) = 0.25, p = 0.25; The number of times the vegetable was tasted and vegetable consumption (follow-up) only among the Fruit Book group, r(21) = 0.44, p = 0.047 (other ps > 0.05); Model adjustments: None; Funding source(s): NR
[underlined: Houston-Price, 2009]^21^; NRCT within-subject design, U.K.; Baseline N= 20; Analytic N= 17; Power analysis: NR; Child characteristics:; - Age: 23.2 months (range= 21.4-24.7); - Female: 50%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: 100% (mothers); - Race/ethnicity: NR; - SEP: NR; Setting: Home-based exposure; Lab taste test; Study objective and primary outcomes: To explore effects of exposure to pictures of familiar and unfamiliar foods on young children’s willingness to taste them. Primary outcome: willingness to taste | Target foods/ Test foods: Book A: grape, blueberry, sweetcorn, radish. Book B: strawberry, lychee, carrot, watercress (familiar and non-familiar foods); Repeated exposure: Non-Taste; 1/d; 2 wk; 14 total exposures; Parent read assigned book with child 5/min per day for 2 weeks; Intervention/control:; - Group A: 2-week intervention. Children received Book A, n=11; - Group B: 2-week intervention. Children received Book B, n=9; Outcomes and assessment methods:; - Willingness to taste foods (n=8) familiar and unfamiliar, exposed and non-exposed were offered.; - Assessment timing: post-intervention (day 15) | [underlined: Willingness to taste, main effect of familiarity]; Significant main effect, p = 0.046, partial ŋ2 = 0.23; Mean intake familiar foods=2.76, SD=1.20; Mean intake unfamiliar foods= 2.24, SD=1.44; *no main effect of exposure, F(1, 16) = .26, p = 0.62, partial ŋ2 = 0.02;; [underlined: Willingness to taste, mean number of foods children tasted]; Familiar exposed foods vs. familiar non-exposed foods, t(16) = 2.14, p = 0.049 ↓; No difference in willingness to taste unfamiliar exposed foods vs. unfamiliar non-exposed foods, t(16) = 0.94, p = 0.36.; Familiar non-exposed foods vs. unfamiliar non-exposed foods, t(16) = 3.05, p = 0.008; ↑; Familiar non-exposed vs. non-familiar non-exposed vegetables: Wilcoxon Z = 2.45, p = 0.007, 1-tailed; ↑; Familiar non-exposed vs. non-familiar non-exposed fruits: Wilcoxon Z = 1.63, p = 0.05 ↑; No difference in familiar exposed foods vs. unfamiliar exposed foods, t(16) = 0.32, p = 0.75; vegetables: Z = 1.13, p = 0.26; fruit: Z = .82, p = 0.41; Model adjustments: None; Funding source(s): NR

a Abbreviations: RCT: Randomized controlled trial; NRCT: non-randomized controlled trial; SEP: Socioeconomic position; g: grams; d: day; wk: week; NR: Not reported; ND: No difference

Table 14 Risk of bias for parallel randomized controlled trials examining repeated exposure to food and food acceptance by infants and young children (birth to 24 months)^a^

Article | Randomization | Deviations from the intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Ahern, 2014^1^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Barends, 2013^2^, 2014^3^ (intake) | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Barends, 2013^2^ (perceived liking) | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Caton, 2013^5^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Coulthard, 2014^6^ | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Fidles, 2015^8^ (intake) | LOW | NOT APPLICABLE | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Fidles, 2015^8^ (liking) | LOW | NOT APPLICABLE | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | HIGH
Forestall, 2007^9^ (intake) | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Forestall, 2007^9^ (perceived liking) | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Gerrish, 2001^10^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Hetherington, 2015^12^ (intake) | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hetherington, 2015^12^ (perceived liking) | SOME CONCERNS | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Mennella, 2008^14^ (intake) | SOME CONCERNS | NOT APPLICABLE | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Mennella, 2008^14^ (perceived liking) | SOME CONCERNS | NOT APPLICABLE | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Paul, 2011^16^ | SOME CONCERNS | NOT APPLICABLE | HIGH | HIGH | LOW | SOME CONCERNS | HIGH
Remy, 2013^17^ (intake) | SOME CONCERNS | LOW | NOT APPLICABLE | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Remy, 2013^17^ (perceived liking) | SOME CONCERNS | LOW | NOT APPLICABLE | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Sullivan, 1994^18^ (intake) | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Sullivan, 1994^18^ (perceived liking) | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Heath, 2014^11^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Houston-Price, 2019^13^ (intake) | SOME CONCERNS | LOW | NOT APPLICABLE | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Houston-Price, 2019^13^ (perceived liking) | SOME CONCERNS | LOW | NOT APPLICABLE | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Owen, 2018^15^ (intake) | SOME CONCERNS | LOW | NOT APPLICABLE | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Owen, 2018^15^ (perceived liking) | SOME CONCERNS | LOW | NOT APPLICABLE | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 15 Risk of bias for cluster randomized controlled trials examining repeated exposure to food and food acceptance by infants and young children (birth to 24 months)^a^

Article | Randomization | Timing of identification and recruitment of individual participants in relation to timing of randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Dazeley, 2015^7^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 16 Risk of bias for non-randomized controlled trials examining repeated exposure to food and food acceptance by infants and young children (birth to 24 months)^a^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Birch, 1998^19^ | SERIOUS | LOW | LOW | MODERATE | NOT APPLICABLE | NO INFORMATION | MODERATE | SERIOUS | SERIOUS
Maier, 2007^20^ (intake) | SERIOUS | LOW | LOW | SERIOUS | NOT APPLICABLE | NO INFORMATION | LOW | MODERATE | SERIOUS
Maier, 2007^20^ (perceived liking) | SERIOUS | LOW | LOW | SERIOUS | NOT APPLICABLE | NO INFORMATION | MODERATE | MODERATE | SERIOUS
Houston-Price, 2009^21^ | SERIOUS | MODERATE | LOW | NOT APPLICABLE | LOW | LOW | LOW | MODERATE | SERIOUS

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 17 Evidence examining the relationship between repeated food exposure and food acceptance by children (2 to 6 years)^a^

Study Information | Intervention, Comparator, Outcome | Results
[underlined: Karagiannaki, 2021]^32^; Cluster RCT, Denmark; Baseline: N=212 (n=8 clusters); Analytic: N=185; Power analysis: NR; Child characteristics:; - Age: 53.8 ± 1.4 mo (3-6 y); - Female: 52%; - Race/Ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/Ethnicity: NR; - SEP: NR; Setting: Kindergartens; Study objectives and primary outcomes: To examine the impact of serving style on the consumption of a raw snack vegetable (daikon) and the influence of its exposure on liking and intake of the vegetable. Primary outcomes: liking, intake, and preference | Target food/ Test food: daikon (unfamiliar); Test foods: daikon, cucumber, celery, broccoli, cauliflower, celeriac and beetroot.; Repeated exposure: Taste; 2/wk; 2wk; 7 exposures; Groups received 100 g of daikon (raw) and children invited to eat as much or as little as they wanted during their afternoon snack. Dummy vegetables: cucumber and celery (served first). Reference vegetable: broccoli, cauliflower, celeriac; daikon and beetroot (served last; randomized order),; Intervention/control groups:; - Daikon sticks: Exposure to 100g of daikon cut into sticks (7 cm length), n=42; - Daikon triangle: Exposure to 100g of daikon cut into triangles (4.5–5 cm length), n=46; - Daikon grated: Exposure to 100g of grated daikon, n=47; - Control group: No exposure to daikon. Visited at baseline, post intervention, at 3- and 6-month follow up, n=50; Outcome measurement and assessment:; - Weighed intake (round slices of daikon, ~4.5 cm), liking: child reported 3-point facial hedonic scale (“like”, “ok” and “dislike” − 1=most preferred and 3=least preferred). , ranking: daikon and beetroot grated, triangle and stick (random order); - Assessment timing: Baseline, post intervention (wk3 and wk8 for control), follow-up (3mo and 6mo) | [underlined: Intake, change from baseline (g) (Mean ± SD)]; Grated daikon: baseline vs. post-test (30 ± 3 vs. 61 ± 5; p ≤ 0.01↑); baseline vs. 3-month follow-up (30 ± 3 vs. 54 ± 5; p ≤ 0.05↑); baseline vs. 6-month follow-up (30 ± 3 vs. 110 ± 6; p ≤ 0.001↑).; Triangle daikon: baseline vs. post-test (26 ± 6 vs. 69 ± 8; NS); baseline vs. 3-month follow-up (26 ± 6 vs. 73 ± 10; NS); baseline vs. 6-month follow-up (26 ± 6 g vs. 110 ± 12; p ≤ 0.001 ↑).; Sticks daikon: baseline vs post-test (17 ± 3 g vs. 111 ± 11; p ≤ 0.001↑). baseline vs. 3-month follow-up (17 ± 3 vs. 89 ± 12; p ≤ 0.001↑). baseline vs. 6-month follow-up (17 ± 3 vs. 118 ± 11; p ≤ 0.001↑).; Control: baseline vs. post-test (13 ± 3 vs. 35 ± 7; p ≤ 0.05↑); baseline vs. 3-month follow-up (13 ± 3 vs. 54 ± 8; p ≤ 0.001↑); baseline vs. 6 mo (85 ± 11; p ≤ 0.001↑).; [underlined: Liking, change from baseline (Mean ± SD)]; Grated daikon: baseline vs. post-test (NS), baseline vs. 3-month (NS); baseline vs. 6 mo (2.0 ± 0.2 vs.2.5 ± 0.1; NS); Triangle daikon: baseline vs. posttest (NR); baseline vs. 3-month follow-up (NR); baseline vs. 6-month follow up (2.0 ± 0.2 vs. 2.8 ± 0.1, p ≤ 0.05)↑; Stick daikon: baseline vs. post-test (1.8 ± 0.2 vs. 2.6 ± 0.1; p = 0.004)↑; baseline vs. 3 mo (1.8 ± 0.2 vs. 2.3 ± 0.1; p = 0.02↑); baseline vs. 6 mo (1.8 ± 0.2 vs. 2.6 ± 0.1; p ≤ 0.01)↑Control group: Baseline to post test (2.0 ± 0.2 vs. 2.5 ± 0.2; NS); baseline vs. 3-month follow up (2.0 ± 0.2 vs. 2.3 ± 0.2; NS); baseline vs, 6-mo (2.0 ± 0.2 vs 2.7 ± 0.1; p ≤ 0.05)↑; [underlined: Liking preference]; ND ranking of daikon shapes (grated, triangle and stick); ND ranking of beetroot shapes (grated, triangle and stick); [underlined: Generalization Effect]; Cauliflower for triangle daikon group:; Baseline vs. post: (2.2 ± 0.2 vs. 2.0 ± 0.2; p ≤ 0.05) ↓; Post vs. 6mo: (2.0 ± 0.2, vs. 1.8 ± 0.2; p ≤ 0.05) ↓; Celery for grated daikon group:; baseline vs. post (1.9 ± 0.2 vs. 1.5 ± 0.1; p ≤ 0.05) ↓; baseline vs. 6-month follow up (1.9 ± 0.2 vs 1.5 ± 0.1; p ≤ 0.05)↓; Broccoli for grated daikon group:; baseline vs. 6-month follow (p ≤ 0.05)↓; Celeriac for triangle daikon group:; Post vs. 6-month follow-up (p ≤ 0.05)↑; Celeriac for stick daikon group:; Baseline vs. 6-month follow-up (p ≤ 0.05)↑; Beetroot for grated daikon group:; Post vs. 6-month follow-up (2.4 ± 0.1 vs. 2.7 ± 0.1; p ≤ 0.05) ↑; Beetroot for triangle daikon group:; Baseline vs. post intervention (p ≤ 0.05) ↑,; Baseline vs. 3-month follow up (p ≤ 0.01)↑; Baseline vs. 6-month follow up (p ≤ 0.01) ↑for group served triangle daikon; Beetroot for stick daikon group:; baseline vs. 3-month follow up (p ≤ 0.05) ↑; Model Adjustments: none; Funding source(s): European Community’s Seventh Framework Programme (FP7/2007–2013) by the Grant Agreement No. FP7-245012-HabEat. The research also received funding from the Nordea -fonden by the project “Taste for Life”.
Karagiannaki, 2021^33^; Cluster RCT, Denmark; Baseline: N=193 (n=8 clusters); Analytic: N=159; Power analysis: NR; Child characteristics:; - Age, Mean, (SD): 55.02 (0.86) (3-6y); - Female: 54%; - Race/ Ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/Ethnicity: NR; - SEP: NR; Setting: Kindergartens; Study Objectives and Primary Outcomes: To investigate different exposure frequencies and compare their effectiveness on increasing the consumption of a novel vegetable by kindergarten children. The study also aimed at investigating whether there are generalization effects from the exposures to other vegetables having more or less sensory characteristics in common with daikon. Primary outcomes: intake and liking | Target food/Test foods: Daikon (unfamiliar); Test foods: Broccoli, Cauliflower, Celeriac, Beetroot (round); Repeated Exposure: Taste; Frequency varies (2x/wk, 1x/wk, 1x/2wk); duration varies 2 to 14 weeks; 7 exposures; Children served 100 g servings (max 200 g) of round sliced daikon in pre-weighed plastic beaker as an afternoon snack.; Intervention groups:; - Twice a week (2x/wk): Exposed to 100 g of grated daikon, n=47; - Once a week (1x/wk): Exposed to 100 g of grated daikon, n=32; - Once every 2 weeks (1x/2wk): Exposed to 100 g of grated daikon, n=30; - Control group: No exposure. Visited at baseline, post intervention, at 3- and 6-month follow up, n=50; Outcomes and assessment methods:; - Weighed Intake, liking; child reported 3-point facial hedonic scale; - Assessment timing: Baseline, post intervention (wk 3 and wk 8 for control), follow-up (3mo and 6mo) | [underlined: Intake of daikon (g), change from baseline] (Mean ± SD); 2x/wk: Baseline (30 ± 3) to; Post-test: 61 ± 5; p = 0.03 ↑; 3-mo follow-up: 54 ± 5; p = 0.02 ↑; 6-mo follow-up: 110 ± 6; p ≤ 0.001 ↑; 1x/wk: Baseline 9 ± 2 to; Post intervention 64 ± 8; p ≤ 0.001↑; 3-month follow-up: 40 ± 8; p ≤ 0.001↑; 6-months follow-up: 82 ± 15; p ≤ 0.001↑; 1x/2wk: baseline 15 ± 5 to; Post-intervention: 75 ± 13; p ≤ 0.001↑; 3-month follow-up: 82 ± 13; p ≤ 0.001↑; 6-month follow-up: 90 ± 11; p ≤ 0.001↑; Control group: Baseline 13 ± 4 to; Post test: 35 ± 7; p = 0.002↑; 3-month follow-up: 54 ± 8; p ≤ 0.001↑; 6-month follow-up: 85 ± 11; p ≤ 0.001 ↑; [underlined: Liking of daikon, change from baseline (Mean ± SD)]; 2x/wk: from baseline (2.0 ± 0.1); Post-intervention (2.6 ± 0.1; p = 0.001↑); 3-month follow-up (2.5 ± 0.1 NS); 6-month follow-up (2.5 ± 0.1 NS).; 1x/wk: from baseline (2.0 ± 0.2) to post-intervention (2.6 ± 0.1, p ≤ 0.001↑); 3-month follow-up (2.6 ± 0.2; NS); 6-month follow-up (2.8 ± 0.1). p ≤ 0.001 ↑).; 1x/2wk: from baseline (1.9 ± 0.2) to post-intervention (2.7 ± 0.2 p = 0.005 ↑),; 3-month follow-up (2.8 ± 0.1 NS); 6-month follow-up (2.7 ± 0.1; p ≤ 0.01↑); Control Group: from baseline (2.0 ± 0.2); to post-intervention (2.5 ± 0.2; NS); 3-month follow-up (2.3 ± 0.2; NS); 6-month follow-up (2.7 ± 0.1; p ≤ 0.05).; [underlined: Generalization Effects to other Vegetables]; 1x/wk: Celeriac compared to post intervention (1.3 ± 0.1) liking at the 3-month follow-up (1.8 ± 0.2; p ≤ 0.05 ↑); 2x/wk: Celeriac compared to post intervention liking at 3-month follow-up (p ≤ 0.05↑).; Control group: Celeriac compared to post intervention liking at 3-month follow-up (p ≤ 0.05↑).; 1x/2wk versus control: Beetroot liking at post-intervention (p ≤ 0.05 ↑),; 1x/wk versus control: Beetroot liking at 3-month follow-up (p ≤ 0.05↑).; Control group: Broccoli liking at baseline and 6-month follow-up (p ≤ 0.05↑) and post-test and 6-month follow-up (p ≤ 0.05↑).; Model adjustment: none; Funding source(s): European Community’s Seventh Framework Programme (FP7/2007–2013) by the Grant Agreement No. FP7-245012-HabEat. The research also received funding from the Nordea-fonden by the project “Taste for Life”.
[underlined: Nekitsing, 2019]^35^; Cluster RCT (2x2 factorial design), U.K.; Baseline N= 219; Analytical N= 140; Power Analysis= NR; Child Characteristics:; - Age: 40.6 ± 0.4 mo (2-5 y); - Female: 57%; - Race/ethnicity: NR; Caregiver Characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: NR; Setting: Preschool; Study objective and primary outcomes: To test the relative efficacy of repeated taste exposure, nutrition education, and a combined TE+NE intervention compared with no intervention control on intake of unfamiliar vegetable. Primary outcome: intake | Target food/Test food: mooli; novel food; Repeated exposure: taste; 1/wk; 12 wks; 10 exposures; Taste exposure: children offered mooli with snack; non-taste exposure: children received nutrition education activities about fruits and vegetables for 10 wks; Mooli was peeled and cut into bite-sized pieces (thin, ~0.4 mm slices) and offered in ~40g portions in a snack bag so child could request more of the vegetable.; Intervention/control groups:; - Taste Exposure (TE): mooli provided at snack time 1/wk every week for 10 weeks in pre-weighed 40-g portions, n=47; - Nutrition Education (NE): staff members delivered existing nutrition education program (phynkyfoods) not directly related to mooli. Staff members instructed to teach 2 specific components of the program as often as possible for 10 weeks. n=38; - Taste Exposure+ Nutrition Education (TE+NE): children offered weekly taste exposures and education program for 10 weeks, n=39; - Control: No intervention during the study period, n=16; Outcomes and assessment methods:; - Weighed intake; - Assessment timing: Baseline (wk1), post-intervention (wk 12), follow-up 1 (wk 24), follow-up 2 (wk 36) | [underlined: Intake, change from baseline]; (Data presented graphically); Children across all conditions ↑ intake from baseline to post-intervention and follow-ups (data presented graphically); [underlined: Intake, amount consumed of the target food among children categorized as eaters (g), mean (SD)]; TE: baseline (n=32) 4.7(1.4); post-intervention (n=44) 17.0 (2.7); Follow-up 1 (n=39) 17.9 (2.7); Follow-up 2 (n=39) 20.1 (2.5);; NE: baseline (n=31) 5.5(1.8); post-intervention (n=38) 8.0 (1.7); Follow-up 1 (n=35) 11.5 (2.1); Follow-up 2 (n=34) 17.6 (2.8);; TE+NE: baseline (n=25) 11.0(2.9); post-intervention(n=35) 17.8 (3.1); Follow-up 1 (n=33) 23.9 (4.0); Follow-up 2 (n=35) 20.8 (2.9); Control: baseline (n=12) 3.5(2.7); post-intervention(n=12) 6.1 (2.8); Follow-up 1 (n=11) 9.5 (4.6); Follow-up 2 (n=12) 10.3 (3.9); [underlined: Predictors of intake among children categorized as eaters]; Effect of condition (P=0.001); intake ↑ in TE condition; Main effect of time (P=0.001); No effect of NE (p=0.49); No interaction effect (P=0.49); Within TE conditions, 10 exposures were sufficient to increase average intake by ~10g. Change was maintained up to 6 mo after intervention phase.; [underlined: Willingness to taste, percentage of children who tasted target vegetable according to intervention group, n (%)]; TE: baseline, 32 (68.1); post-intervention, 44(93.6); follow-up 1, 39 (83.0); follow-up 2, 39 (83.0); NE: baseline, 31 (81.6); post-intervention, 38(100.0); follow-up 1, 35 (92.1); follow-up 2, 34 (89.5); TE+NE: baseline, 25 (64.1); post-intervention, 35(89.7); follow-up 1, 33 (84.6); follow-up 2, 35 (89.7); Control: baseline, 12 (75.0); post-intervention, 12 (75.0); follow-up 1, 11 (68.8); follow-up 2, 12 (75.0); [underlined: Willingness to taste, logistic regression predicting eater status at post-intervention]; Main effect of condition: Interaction between TE and NE (χ2 [1]=4.67, P=0.031); children in control condition less likely to be eaters than any of the other intervention conditions; NE and TE+NE higher odds of being eaters than TE and Control; (OR 6.43, 95% CI 1.5 to 27.8; χ2 [1]=5.73; P=0.017); TE did not affect eater status: (OR 1.65, 95% CI 0.37 to 7.44; χ2 [1]=0.24; P=0.63); Main effect of time: χ2 [2]=5.82; P=0.054, No main effect.; Model adjustments: corrected for cluster assignment; age and baseline intake (for intake analysis); Funding source(s): White Rose Doctoral Training Center (WRDTC) Economic and Social Research Council (ESRC) Collaborative Award. Collaborative Partner is Purely Nutrition Ltd.
[underlined: Nekitsing, 2019]^34^; Cluster RCT (2x2 factorial parallel design), U.K.; Baseline N= 337 ^Re^; Analytic N= 267^exp^; Power analysis: small-medium effect size (Cohen’s f=0.20), 80% power, α=0.05, sample size needed= 199 (at least n=50/condition); Child characteristics:; - Age: 38 ± 0.5 mo (2-5 y); - Female: 44.6%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: NR; Setting: Preschools; Study objective and primary outcomes: To examine the combined effects of learning about an unfamiliar vegetable through illustrated storybooks with sensory play on recognition and intake of that “target” vegetable. Primary outcome: celeriac intake | Target food/ Test Foods: Celeriac (unfamiliar vegetable), Test: carrot; peated exposure: Non-taste; 1/d; 2 weeks; 11 exposures; Preschool staff read a storybook with either congruent (celeriac) or incongruent (carrot) vegetable story. Children allocated to the sensory play condition (sound, sight, touch and smell) also were encouraged to explore and play with the vegetable. Storybooks were read a minimum of 5 times and remained on display to increase visual exposure throughout the intervention.; intervention /control groups:; - Congruent storybook: 2 activity sessions (day 1 and day 15) and familiarization phase (day 2-14) consisting of reading celeriac story (congruent vegetable), n=59; - Congruent storybook plus congruent sensory: 2 activity sessions (day 1 and day 15) consisting of reading celeriac story and celeriac sensory activity (congruent vegetable) and familiarization phase (day 2-14) consisting of reading celeriac story, n=66; - Incongruent storybook: 2 activity sessions (day 1 and day 15) and familiarization phase (day 2-14) consisting of reading carrot story (incongruent vegetable), n=65; - Incongruent storybook plus incongruent sensory: 2 activity sessions (day 1 and day 15) consisting of reading carrot story and carrot sensory activity and familiarization phase (day 2-14) consisting of reading carrot story (incongruent vegetable), n=77; Outcomes and assessment methods:; - Weighed intake, Willingness to taste; likelihood of consuming any celeriac (scale 1-9); - Assessment timing: baseline (day 1) and post-intervention (day 15) | [underlined: Intake, group comparisons]; - Median celeriac intake (all children) (g) increased for congruent storybook, congruent storybook + congruent sensory and incongruent storybook + incongruent sensory (medians reported in figure); - Mean intakes at post-intervention (eaters only) (SD) g: congruent storybook 8.45 (1.5), congruent storybook plus congruent sensory play 11.27 (14.63), incongruent storybook 10.79 (14.65), incongruent storybook with incongruent sensory play 9.31 (10.47); - No effect of congruency or sensory play, or interaction on post—intervention intakes; - Effect of age on post-intervention intake (b=0.24; P=0.03); - Effect of baseline intake on post-intervention intake (b=0.68; P<0.001); [underlined: Willingness to taste, group comparisons (congruent vs. incongruent story book)]; - % of eaters ↑ (69% vs. 83%); - More likely to be eaters post-intervention (odds ratio [OR] 1.16; 95% CI: 0.56, 2.40; χ2 [1]=16.60; P<0.001); - Effects of sensory play on likelihood of consuming celeriac: no effect (OR 0.78; 95% CI: 0.38,1.57; χ2 [1]=2.70; P=0.1); - Interaction between storybook and sensory play: (OR 3.25; 95% CI: 1.47, 7.23; χ2 [1]= 9.45; P=0.002) * children receiving congruent storybook and congruent sensory play more likely to be eaters; [underlined: Subgroup analysis with baseline non-eaters]; - Percentage of children (non-eaters at baseline) who ate something at post-intervention was higher in sensory conditions (63%) vs. storybook-only conditions (38%) (P<0.001); - No interaction between congruency and sensory play on likelihood of being an eater for this subgroup (non-eaters at baseline); Model adjustments: clustering into preschools, age, baseline consumption; Funding source(s): White Rose Doctoral Training Centre (WRDTC) Economic and Social Research Council (ESRC) Collaborative Award; PhunkyFoods; Purely Nutrition Ltd
[underlined: Van Belkom, 2023]^36^; Cluster RCT, Netherlands; Baseline N= 598 (26 day-cares); Analytic N= 447; Power analysis: For medium effect size (f = 0.25), 95% power, and α=0.05, sample size needed n=189; Child characteristics:; - Age: 2.6 ± 0.59 y (1-4 y); - Female: NR; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: NR; Setting: Day-care centers; Study objective and primary outcomes: To examine the effect of a repeated exposure program with (‘exposure/reward’) or without (‘exposure/no reward’) contingent non-food rewards on the willingness to try vegetables relative to a no intervention control condition (‘no exposure/no reward’). Primary outcome: WTT | Target food/ Test Foods: tomato, cucumber, carrot, bell pepper, radish and cauliflower; 4 familiar (assessed at group level), 2 novel; Test: tomato, cucumber, carrot, bell pepper, broccoli, cauliflower, green beans, pumpkin, radish, celeriac, eggplant, beetroot and corn.; Repeated exposure: Taste; 1/d; 3M; at least 5 exposures to each vegetable; Children offered 5 pieces of 2-4 vegetables every day for 3 mo. Childcare workers selected which vegetables from list to offer each day. Repeated exposure was done at a fixed time point, approx. 30 minutes per day in place of usual snack. Vegetables were offered as bite sized pieces); Intervention/ control groups:; - Exposure/reward: (3 mo exposure) children received 2-4 different raw vegetables per day at day-care during normal snack time. Children offered 5 pieces of each vegetable. Children offered sticker each time they were willing to taste 1 of the vegetables with max 1 sticker per vegetable per day. When child tried specific vegetable 5 times, they received additional card and named vegetable king/queen, n=233; - Exposure/ no reward: (3 mo exposure) children received 2-4 different raw vegetables per day at day-care during normal snack time. Children offered 5 pieces of each offered vegetables, n=213; - No exposure/ no reward: no specific instructions on offering daily set of vegetables, n=152; Outcomes and assessment methods:; - Willingness to taste, children offered up to 2 bites of 6 Test vegetables. If 1^st^ bite accepted, child offered 2^nd^ bite (max score= 12 points); - Assessment timing: baseline and post-intervention | [underlined: Willingness to taste, mixed effects model with condition and time (baseline vs. post-intervention)]; Main effect of time (pre and post-test), P=0.02; Condition x Time interaction p < 0.001; [underlined: Group differences, relative to control (no exposure/ no reward):]; (Data presented graphically); Exposure/reward: Estimate 2.22, SE 0.59, 95% CI: (1.06-3.38) ↑; ND Exposure/No reward: Estimate 1.06, SE 0.60, 95% CI: (−0.12-2.25); Model adjustments: day care center as random effect; Funding source(s): Dutch Province of Limburg, Region Deal Noord-Limburg, Scelta Mushrooms, Seacon Logistics, Rabobank Noord-Limburg, Royal ZON, BASF’s Vegetable Seeds business, and the Jacques & Ellen Scheuten Foundation
[underlined: Bouhlal, 2014]^23^; Cluster RCT, France; Baseline N= 157; Analytic N=151; Power analysis: NR; Child characteristics:; - Age: ~27.1 mo (2-3 y); - Female: 45%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: NR; Setting: nursery schools; Study objective and primary outcomes: To compare the effect of repeated exposure to that of flavor-flavor learning, on the acceptance of a non-familiar vegetable by 2- to 3-year-olds in a natural context, on the short term and up to 6 mo after the exposure period. Primary outcomes: intake and liking | Target food/ Test Foods: salsify, low familiarity & neutrally appreciated (judged by mother); test food: carrot; Repeated exposure: Taste; 2/wk; 6 wk; 8 total exposures; Salsify puree samples: basic recipe prepared with 0.2% w/w salt, salty recipe prepare with 0.5% w/w salt, the nutmeg recipe was prepared with 0.2% w/w salt+ 0.02% w/w nutmeg, The unseasoned carrot puree samples were prepared with 0.2% w/w salt. Study foods were presented as a started at beginning of young children’s lunch (100g jars); Intervention/control groups:; - Repeated Exposure (RE): exposed to basic salsify puree, n=47; - Flavor-Flavor learning with salt (FF-salt): exposed to basic salsify puree with added salt, n=54; - Flavor-Flavor learning with nutmeg (FFL-Nutmeg): exposed to basic salsify puree with added nutmeg, n=50; Outcomes and assessment methods:; - Weighed intake, liking: caregiver (teacher) report using 5-point likert scale (−2, dislikes very much to 2, likes very much); - Assessment timing: Baseline and posttest (1 month for target vegetable, 3 and 6 mo for target and control vegetable, served in a counterbalanced order) | [underlined: Intake of basic salsify puree (g), group differences (mean ± SD)]; ND between groups at baseline, P=0.48; Increase in intake from baseline to 1^st^ exposure RE group (25 ± 9), P=0.002; Effect of exposure (1^st^ through 8^th^ exposure) on intake for RE group, P=0.003 ↑ (4.5 ± 1.5 per exposure); ND mean intake between groups during exposure period (106 ± 7), P=0.87; ND 8^th^ exposure to post-intervention in RE group, P=0.93; Mean increase pre- to post-intervention across all groups 41±7; Significant group effect on change pre- to post- intervention, P=0.03;; Higher increase in intake pre- to post-intervention for RE group (64 ± 11) compared with FFL-Salt group (23 ± 11; P=0.009), FFL-Nutmeg groups (36 ± 11; P=0.07); No group effect (P=0.42) or exposure number effect (P=0.49) on change in carrot puree intake from pre- to post- intervention; [underlined: Liking of basic salsify puree, group differences]; ND between groups at baseline, P=0.95; ND liking from baseline to 1^st^ exposure for RE group, P=0.17; Effect of exposure (1^st^ through 8^th^ exposure) on liking for all groups, P<0.001 ↑; ND mean liking between groups during exposure period (0.8 ± 0.1), P=0.88; ND liking 8^th^ exposure to post-intervention in RE group, P=0.16; Difference in mean liking at post-intervention between groups, P=0.013; mean liking pre- to post- intervention higher in RE group than other 2 groups (data presented graphically); ND mean increase in liking between groups (0.7±0.1), P=0.17, no effect of exposure P=0.31; Increase in liking pre- to post- exposure for RE group, P<0.0001; No group effect (P=0.07) or exposure number effect (P=0.09) on change in carrot puree liking from pre- to post-intervention; [underlined: Acceptance of carrot puree, group differences]; At baseline, ND, P=0.97; From the 3-month follow-up on, increase in FFL-Salt group compared to RE and FFL-Nutmeg groups, p < .0001;; Liking, no change from post-exposure to the 3- and 6-month follow-ups for all groups, except in the FFL-Salt group, for whom a significant increase was observed at the 6-month follow-up but did not differ from the changes observed in the 2 other groups.; [underlined: Intake and Liking of salsify at 1, 3, and 6 month follow up]; ND intake post-intervention and 1-, 3- and 6 month follow ups (all groups); Liking Post-intervention vs. 6-month follow up (0.4±2), P<0.05 ↓ ND liking post-intervention vs. 1- or 3-month follow-up; ND liking (carrot) post-intervention to 3- and 6-month follow-up for all groups; Model adjustments: nursery effect; Funding source(s): European Community’s Seventh Framework Programme, Regional Council of Burgundy France and FEDER
[underlined: Byrne, 2002]^24^; Cluster RCT, US; Baseline N=118 (n= 9 clusters); Analytic N=86; Power Analysis: NR; Child characteristics:; - Age: 3-5 y; - Female: NR; - Race/ethnicity: 37% white, 38% black, 14% Latino, 10% Asian, 2% NA/ Alaskan/ Hawaiian; * Children recruited from 9 Head Start classes; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: NR; Setting: university preschool; Study objective and primary outcomes: To investigate whether children’s books affect (1) the willingness of each child to taste a target novel vegetable (kohlrabi) during 1 pretest and 2 posttest interviews and (2) the attitudes of the child regarding the target novel vegetable. Primary outcomes; WTT and attitudes toward vegetable | Target food/ Test food: kohlrabi; novel food; Repeated exposure: Non-taste; 1/d, 2 days, 2 exposures; Teachers read modified book about kohlrabi to class as group followed by individual interviews to assess willingness to taste and attitude regarding kohlrabi. Kohlrabi was presented as whole kohlrabi and peeled and cut into sticks.; Intervention/control groups:; - Positive message group: 2 exposures to modified book containing (positive) distinct and repeated messages about target vegetable followed by posttest (day 2 and 3), n=29; - Negative message group: 2 exposures to modified book containing (negative) distinct and repeated messages about target vegetable followed by posttest (day 2 and 3), n=29; - Control group: 2 exposures to book that did not mention food followed by posttest (day 2 and 3), n=28; Outcomes and assessment methods:; - General vegetable attitudes measured by 4-level hedonic scale (happy and sad faces); willingness to taste target vegetable (taste any portion of kohlrabi sticks); - Assessment timing: Baseline, day 2 and day 3 | [underlined: Willingness to taste, percent (n) of children]; Positive message group: Pretest=90 (26), Posttest 1= 83 (24), Posttest 2= 90 (26); posttest 2 vs. posttest 1, P<0.05; Negative message group: Pretest= 62 (18), Posttest 1= 62 (18), Posttest 2= 69 (20); posttest 2 vs. posttest 1, P<0.05 and posttest 2 vs. pretest, P<0.05; Control: Pretest=75 (21), Posttest 1=57 (16), Posttest 2= 61 (17); posttest 2 vs. pretest, P<0.05; Percentage of positive-message subjects WTT was significantly greater than percentage of control subjects WTT at posttest 2 (P<0.05); [underlined: Willingness to taste at Posttest 2]; Significant factors in final model:; Intention to taste again during first posttest (P=0.0026); Being a member of positive message group (P=0.398); Residual chi-square= 0.8834; chi-square=16.126, P<0.001; [underlined: Attitudes about kohlrabi]; Pretest (n=69): 72% liked kohlrabi; (No information provided about liking at posttest); Model Adjustments: none; Funding source(s): College of Agricultural and Life Sciences at the University of Wisconsin Madison
[underlined: Coulthard, 2018]^27^; Cluster RCT, U.K.; Baseline N= 100 (n=10 clusters); Analytic N=83; Power analysis: NR; Child characteristics:; - Age: 2.75 ± 0.82 y; - Female: 54%; - Race/ethnicity: 82% white British, 7% white European, 5% South Asian, 6% mixed; Caregiver characteristics:; - Age: 33.97 ± 0.82 y; - Female: NR; - Race/ethnicity: NR; - Education (years): 16.06 (3.58); - Parental FV (portion/d): 3.72 (1.99); Setting: preschool; Study objective and primary outcomes: to examine whether an intervention based on sensory play would be associated with increased fruit consumption in preschool children. Primary outcome: fruit enjoyment (perceived liking) | Target food/ Test Foods: raspberry, test: banana (familiar), lychee (novel); Repeated exposure: Taste & Non-taste; 1/wk; 5 wk; 5 exposures; 1x/ week for 5 weeks, children participated in a fruit play task (single fruit: blueberry, prunes, raspberry, passion fruit, melon) and/ or a taste test with matching fruit (presented after sensory play activities, small piece (~2cm); Intervention/control groups:; - Combined sensory play with exposure: 5 different food play tasks (1/wk) and taste exposure to 5 fruits (same as sensory play) (1/wk), n=21; - Non-food sensory play with exposure: 5 different non-food sensory tasks (1/wk) and taste exposures to 5 fruits (1/wk), n=20; - Taste Exposure: Taste exposures to 5 fruits, n=21; - Control, completed non-food related games (shape sorting, ring game, jigsaw puzzle, block building) n=21; Outcomes and assessment methods:; - Perceived liking (mean of parent and experimenter rating, 1-5 scale). Difference acceptance score: difference of taste test enjoyment score from parent rating of how much food was normally liked (1-5; 0 if never tried) (−5-5 scale); - Assessment timing: 6-wk post-intervention | [underlined: Perceived liking, group comparisons post-intervention]; Differences between groups in total fruit enjoyment across groups, p < 0.05, η_p_^2^ = 0.18 (large effect size); Differences between groups in target fruit enjoyment (raspberry) across groups (effect size not provided); Raspberry liking sensory play conditions vs. control group, (P<0.05) ↑; Combined sensory play + taste exposure vs. control (mean, SD): 0.53(1.62) vs. −0.70(1.34), p<0.05; Non-food sensory play +taste exposure vs. control: 0.24(1.37) vs. −0.70(1.34), p<0.05; ND raspberry liking taste exposure group vs. control; Differences between groups in novel fruit enjoyment (lychee) across groups, p < 0.05, η_p_^2^ = 0.12 (moderate effect size); taste exposure group vs. control (mean, SD): 0.94 (2.05) vs. 1.33 (1.85), p<0.05; Banana liking non-food sensory play condition vs. control: - 0.13(0.64) vs. −1.55(2.01), p<0.05; Total fruit liking combined sensory play + taste exposure vs. control: 1.12 (1.65) vs −0.93 (4.07), P<0.05; non-food sensory play + taste exposure vs. control, 2.76 (2.64) vs. - 0.93 (4.07), P<0.05; Model adjustments: age of child, baseline range of fruits accepted.; Funding source(s): Feeding for Life Foundation (Danone)
[underlined: Hausner, 2012]^29^; Cluster RCT, Denmark; Baseline N=104; Analytic N= 85, (N=71 at 6 mo); Power analysis: NR; Child characteristics:; - Age: ~28.6 mo (2-3 y); - Female: 52.8%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: NR; Setting: Nursery; Study objective and primary outcomes: to investigate acceptance learning in 2–3-year-old children by comparing the mere exposure, flavor–flavor learning and flavor– nutrient learning strategies to increase acceptance of a novel vegetable. Primary outcome: intake. | Target food/ Test Foods: Artichoke puree (unmodified, sweetened, added fat; low familiarity, neutral appreciation); Test vegetables: carrot puree (familiar, liked); Repeated exposure: Taste; 2-3x/week; 28 days; 10 exposures; Children were served either unmodified artichoke purée, a sweetened or energy dense artichoke purée 2-3 times a week before lunch over a period of 4 weeks.; Intervention /control groups:; - Mere exposure group (MExp): exposed to unmodified artichoke puree 10 times, n=32; - Flavour–flavour learning group (FFL): exposed to a sweetened artichoke puree (added sucrose) 10 times, n=33; - Flavour– nutrient learning group (FNL): exposed to an energy dense artichoke purée with added fat (sunflower oil) 10 times, n=39; Outcomes and assessment methods:; - Weighed intake; - Assessment timing: pre/post-intervention (3 days after 10^th^ exposure), 3-month follow-up and 6-month follow-up | [underlined: Intake of 3 artichoke purées, group differences:]; First exposure, ND (data presented graphically); 5th exposure, ND; 10^th^ exposure, energy dense purée vs. unmodified (p = .012)↓ and energy dense vs. sweet purée (p = .0007) ↓; [underlined: Intake of respective purée, pre/po]st-intervention; Unmodified purée group, across exposure, P = 0.0022 ↑; MExp group (unmodified purée), first to 5^th^ exposure, p = .0035 ↑; 5th to the 10th exposure, ND; FFL group (sweet purée), across exposures, p < .0001 ↑; 1st (14 g) to the 5th exposure (53 g), ND; 5th to the 10th exposure (148 g), p = .0016 ↑.; FNL group (energy dense purée), 1st to the 5th exposure, NS; 5^th^ to the 10^th^ exposure, ND; [underlined: Intake of unmodified purée (post-intervention, 3 and 6 mo follow-up):]; Pre-to post-intervention: MExp, p = .0005 ↑; FFL (F(2,32) = 29.9, p = .0060↑; FNL, ND; 10^th^ exposure to post-intervention: MExp group, NS; FFL group consumed ↓ (t(37) = 2.34, p = .0246); FNL group, ND; Post-intervetnion, group differences: MExp vs. FFL, NS; MExp vs. FNL group, p = .0032 ↑; MExp vs. FNL, p = .050↑; Post-intervetnion to 3 mo follow-up: MExp group, ND; FFL group, ND; FNL group, ND; post-intervetnion to 6 mo follow-up: MExp group, ND; FFL group, ND; FNL group, ND; 3 mo follow-up, group differences: MExp group vs. FFL, p = .0463 ↑; MExp vs. FNL, p = .0021 ↑; 6 mo follow-up, group differences: ND due to large inter-individual intake differences; [underlined: Intake of carrot purée (post-intervetnion, 3 and 6 mo follow-up):]; Pre- to post-intervention: No group differences; Pre-intervention to 6 mo follow-up: FNL group, p = .0071 ↑.; Post-intervention to 3 mo follow-up: MExp group, P=NR (data presented graphically) ↑; FFL group, p= p = .0152↑; FNL, ND; Post-intervention to 6 mo follow-up: MExp group, p = .0332 ↑;; FFL group, p = .0040 ↑; 3 to 6 mo follow-up: no group differences.; 3 mo follow-up, group differences: MExp vs. FNL group, p = .0022 ↑; FFL vs. FNL group, p=0021 ↑; 6 mo follow-up, group differences: No group differences due to large inter-individual differences within the study groups.; Model adjustments: age (mo) and gender; Funding source(s): the European Community’s Seventh Framework Programme (FP7/2007-2013) under the Grant Agreement No. FP7-245012-HabEat
[underlined: Hoppu, 2015]^31^; Cluster RCT, Finland; Baseline N= 68; Analytic N= 56; Power analysis: NR; Child characteristics:; - Age: ~5.0 y (3-6 y); - Female: 53%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: ~34.0y; - Female: 100%; - Race/ethnicity: NR; - SEP: ~25% university or polytechnic degree; ~75% employment, working; Setting: kindergartens; Study objective and primary outcomes: To evaluate the effectiveness of sensory-based food education in a kindergarten with no previous experience with these activities. Primary outcome: Willingness to try test vegetables and berries | Target food/ Test Foods: carrots, cabbage, swede, rucola, romaine lettuce, lingonberry, and bilberry (not included in sensory activities) and sea buckthorn (juice; not included in sensory activities)); Repeated exposure: Non-taste & taste; 1/wk; 5 weeks; 5 exposures; Food education sessions delivered in kindergartens. Sessions lasted 20-30 minutes focused on activating all 5 senses. Sessions included tasting and exploration of food samples (carrots, cabbage, swede, rucola, romaine lettuce and lingonberries); Intervention/control groups:; - Intervention: Children received 5 sensory based food education sessions focusing on vegetables and berries with tasting and exploration of food samples (1/wk), n=37; - Control: No activities, n=19; Outcomes and assessment methods:; - Willingness to taste: Sample of cut vegetable pieces (10g/ piece) or strips (4-5 strips) and berries (slightly) defrosted (10g/serving). Vegetables served first, followed by berries. Children allowed to decide which order they would taste. Amount eaten was categorized as proportion of sample eaten (not tasted/ tasted a bit/ ate half the sample/ ate the whole sample); - Assessment timing: baseline and post-intervention (wk 5) | [underlined: Willingness to taste, group differences (%)]; Intervention group; Significant difference in distribution (P< 0.001, Friedman’s) and median of differences (p<0.001, Wilcoxon) between measurements at baseline and post-intervention; Proportion of samples completely eaten increased significantly (p<0.001)↑; Willingness to eat carrots (p<0.001) ↑; Willingness to eat swede (p=0.004) ↑; ND: Willingness to eat cabbage, rucola, romaine lettuce; Willingness to eat bilberries (p<0.001) ↑; Significant difference in median intake of carrots (p=0.001), cabbage (0.039), swede (0.022), and rucola (p=0.048) (wilcoxon); ND in median intake of romaine lettuce; Control group; ND willingness to eat (total amount of all samples) between baseline and post-intervention; Willingness to eat romaine lettuce (p=0.033; Wilcoxan, p=0.034; Friedman) ↑; No other differences in willingness to eat individual vegetables/ fruits; Model adjustments: none; Funding source(s): Academy of Finland
[underlined: Holley, 2015]^30^; Cluster RCT, U.K.; Baseline N=136; Analytic N=115; Power analysis: Minimum of 16 dyads per condition to detect small effect with power 0.8 and p<0.05; Child characteristics:; - Age: 38 ± 7.75 mo; - Female: 58.2%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: ~35.9 (2-4 y); - Female: NR; - Race/ethnicity: 85.2% white/Caucasian, 5.2% black/Black British, 1.7% Asian/Asian British, 7.8% did not provide information; - SEP: 47.0% non-University graduates; 53.0% University level or higher; Setting: Home; Study objective and primary outcomes: To evaluate the intervention’s success at increasing children’s liking and consumption of a previously disliked vegetable. Primary outcomes: Liking and intake. | Target food/ Test Foods: disliked vegetable (ranked 4th by parent out of 6 vegetables: Baby corn, celery, red pepper, cherry tomato, cucumber, sugar snap peas; Not a disliked vegetable by parent).; Repeated exposure: Taste; 1/d; 14 d; 14 exposures (min 10 exposures); Parent provided daily offerings (small piece, ~2.5g) of a disliked vegetable in their raw form, chopped. Vegetables were provided outside of mealtimes.; Intervention/control groups:; - Repeated Exposure: Parents instructed to offer target vegetable without eating it themselves, n=25; - Modelling and Repeated Exposure: Parents instructed to eat a small piece of the target vegetable in from of their child, expressing a positive response, and then offer their child a small piece, n=24; - Rewards and Repeated Exposure: Parents instructed to offer their child a small piece of the target vegetable, telling them that if they try a small piece they can choose a sticker, n=25; - Modelling, Rewards and Repeated Exposure: parents instructed to eat a piece of the target vegetable in front of their child, saying how nice it was, then offer their child a piece telling them they could choose a sticker if they tried it, n=23; - Control: no-treatment group, n=18; Outcomes and assessment methods:; - Weighed intake; liking: 3-point smiley face scale; - Assessment timing: baseline and post-intervention | [underlined: Intake, baseline vs. post-intervention (g), Mean (SD):]; Consumption of target vegetable increased for all groups, main effect of time, p<0.001 ↑; Repeated exposure: 0.28 (0.78) vs. 2.90 (5.30); Modeling & repeated exposure: 0.36 (0.60) vs. 4.68 (8.37); Rewards & repeated exposure: 0.48 (0.87) vs. 3.65 (6.83); Modeling, rewards & repeated exposure: 0.61 (1.06) vs. 3.96 (5.64); Control: 0.25 (0.54) vs. 1.14 (1.92); No group x time interaction on intake; ND in post-intervention intakes between groups; Post-intervention intake significantly higher for modeling, rewards & repeated exposure group vs. control (Mann-Whitney U test; Mdn=1.65 vs. 0.00, U=137.00, z= −1.98, p=0.02, r=-0.31) and rewards& repeated exposure vs. control group (Mann-Whitney U test; Mdn= 0.50 vs. 0.00, U=155.0, z=-1.82, p=0.03, r=0.28).; ND in post-intervention consumption in modeling or repeated exposure groups vs. control group; [underlined: Liking, group comparisons (n=76)]; No baseline differences in liking between 5 groups; Significant differences in rated liking at post-intervention between groups, χ2 (8, N = 76) = 15.48, p = 0.05, V = 0.32; Proportion of children who rated target vegetable as ‘yummy’ was highest in modeling, rewards & repeated exposure group and rewards and repeated exposure (over 60%), intermediated in modeling and repeated exposure and repeated exposure groups (over 26%) and lowest in control group (10%); Model adjustments: none; Funding source(s): Not reported
[underlined: O’Connell, 2012]^25^; Cluster RCT, U.S.; Baseline N= NR (n=2 clusters); Analytic N=96; Power analysis: medium effect size between 2 groups indicated n=100; Child characteristics:; - Age: 85% of children 4-5 y; - Female: 43.8%; - Race/ethnicity: 69% white, 8% Asian, 5% African American, 6% Hispanic, 12% other; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: 93% at least 1 parent with bachelor’s degree; 75% at least 1 parent with graduate/professional degree; Setting: Preschools (both participate in Child and Adult Care Food Program, CACFP, that provides all meals and snacks); Study objective and primary outcomes: To test whether children in a community preschool would increase consumption of 3 unfamiliar or disliked vegetables after being offered each of them 10 times during lunch over a 6-week period. Primary outcomes: vegetable intake | Target food/ Test Foods: cauliflower, snow peas, green pepper. unfamiliar/disliked; Repeated exposure: Taste; 1/d; 30 days; 10 exposures/vegetable; Pre-portioned snack bags (24-26 g) of vegetables (raw, cut into bite-sized pieces) were distributed to children with lunch meal in place of produce from CACFP reimbursable lunches.; Intervention/control groups:; - Intervention group: children served 1 vegetable every day in a 3-day cycle, n=43; - Control: no change/routine foods for week 1-6, week 6-12 received delayed intervention (same procedures as intervention group), n=53; Outcomes and assessment methods:; - Weighed intake; - Assessment timing: baseline, post-intervention (week 6) | [underlined: Intake, baseline vs. post-intervention (g), Mean ± SD]; Intervention group 10.7 ± 8.5 vs. 8.5 ± 6.8; control group 6.2 ± 6 vs. 7.5 ±7.4; [underlined: Intake, group comparisons (g)]; Significant time x condition interaction on intake (average across 3 vegetables); control group ↑, intervention group ↓ , P=0.002; Baseline vs. post-intervention change by vegetable:; Snow peas, No change in intervention or control group; Cauliflower: intervention group (−4g, F[1,82]=7.67, P=0.007)↓ and no change in control group; Green peppers: no change in intervention group, control group (P=0.004)↑; [underlined: Intake, variability over time]; The amount of variance between subjects ranged from 57% to 62%, and, conversely, the proportion of variance within subjects across time ranged from 38% to 43% across the 3 vegetables.; Model adjustments: NR; Funding source(s): Rudd Foundation
[underlined: Vandeweghe, 2018]^37^; Cluster RCT, Belgium; Baseline N= NR; Analytic N= 154 (n= 8 clusters); Power analysis: NR; Child characteristics:; - Age: 5.08 ± 0.61 y; - Female: 53.2%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP:NR; Setting: pre-schools; Study objective and primary outcomes: To investigate the effectiveness of different strategies (i.e. Repeated Neutral Exposure (RNE), Repeated Exposure (RE) + token reward and RE + social reward) in preschool children. Primary outcome: willingness to taste, liking after having tasted the vegetable, change in liking and intake. | Target food/ Test Foods: chicory; disliked; Repeated exposure: Taste; 1/d; 2/wk, 4 wk; 8 exposures; Children offered bowl (60g) of chicory before snack time. Taste trials (exposures) were performed individually. Children were offered small portion (± 4 g) steamed chicory. The way the chicory was offered (neutral/ reward/) differed dependent on the allocated condition. Each tasting trial lasted approx. 3 min.; Intervention/control groups:; - Repeated Neutral Exposure: 8 exposures, child was asked neutrally to taste the chicory, n=31; - Repeated Exposure + social reward: 8 exposures, child received social approval (verbal encouragement) when he/she tasted, n=46; - Repeated Exposure + token reward: 8 exposures, child could earn a sticker if he/she tasted. When child received enough stickers, he/she could receive a toy, n=41; - Control: No tasting trials took place, n=36; Outcomes and assessment methods:; - Weighed intake, liking: child rating using cartoon drawings of facial expressions (‘yummy’, ‘just okay’, ‘yucky’), willingness to taste: percentage of trials during which a child tasted chicory; - Assessment timing: baseline, post-test, 8-week follow-up | [underlined: Intake, group differences at baseline post-intervention and follow-up (data presented graphically)]; Group differences at baseline, ND; Condition x time interaction, (p < .001); Group differences at post intervention and follow-up, intervention conditions vs. control at post-intervention (p’s for all pairwise comparisons <0.028)↑; Group differences, groups at any timepoint, 3 intervention groups, ND; [underlined: Liking, group differences at baseline, post-intervention, and follow-up]; [underlined: (Data presented graphically)]; Groups differences at baseline, ND; Condition x time interaction, (p < 0.020); Group differences, at post-intervention and follow-up,; Probability of liking on 3 intervention conditions vs. control (p’s for all pairwise comparisons < 0.006) ↑; Group differences, groups at any timepoint, 3 intervention groups, ND; [underlined: Willingness to taste, group differences]; Percentage of trials that a child tasted between 3 intervention conditions, ND; Comparison with control, data NR; Model adjustments: reward sensitivity; Funding source(s): Agency for Innovation by Science and Technology (IWT) of Flanders, in the project Reward – Rewarding Healthy Food Choices.
[underlined: Zeinstra, 2018]^39^; Cluster RCT, Netherlands; Baseline N= 446; Analytic N=250 (n=4 clusters); Power analysis: (p=0.05; power 80%; SD of 35 g) aiming for clinically relevant increase in children’s vegetable consumption of 15 g indicated 67 children per condition; Child characteristics:; - Age: ~25.3 mo (3-6 y); - Female: 40%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - Education: 0% primary/secondary school; 7.2% vocational education; 92.7% higher vocational or university degree; Setting: childcare centers; Study objective and primary outcomes: To investigate the effect of repeated exposure to 3 a priori unfamiliar vegetables presented singly in the daily routine of a childcare setting on children’s vegetable acceptance. Primary outcome: vegetable acceptance. | Target food/ Test Foods: pumpkin, zucchini, white radish; unfamiliar vegetable; Repeated exposure: Taste; 1/d; 21 weeks; 10 exposures/vegetable (average 6 exposures to each vegetable product); For baseline and post-test: ad libitum vegetable intake. Pumpkin and zucchini were offered blanched and white radish raw. For exposure:; Pumkin blanched (100g) and as a cracker spread (100g); zucchini blanched (100g) and as soup (100g); white radish raw (100g) and as a cracker spread (100g). 1 vegetable was offered per day as afternoon snack.; Intervention/control groups:; - Intervention group: 21-week exposure period, children offered vegetable as afternoon snack (2 preparations per vegetable), n=125; - Control group: 21-week exposure period, children kept their regular eating routines (familiar raw vegetables in afternoon, i.e. tomatoes, cucumber, red bell pepper), n=125; Outcomes and assessment methods:; - Weighed intake, willingness to taste: childcare employees registered whether child tasted vegetable or not, defined as placing food in the mouth or licking food; - Assessment timing: baseline and post-test (4 weeks each; expected to cover all children and all 3 vegetables at least twice).; Vegetables offered randomly on condition that each vegetable covered all 5 weekdays evenly and no vegetable offered more than 2x/wk | [underlined: Intake, baseline vs. post-test]; Significant time x condition interaction for pumpkin ( p < 0.001) and white radish (F(1,207) = 6.79 p = 0.01); No significant intervention effect for zucchini; Intervention group: pumpkin (+15 g, ~88%; t(100) = −6.07; p < 0.001)↑ and white radish ( + 16 g ~ 178%; t(96) = −6.97; p < 0.001)↑. No difference in zucchini; Control group: white radish p (+ 7 g ~ 57%; t(82) = −3.55; p = 0.001)↑. No difference in pumpkin or zucchini; Change in white radish intake significantly positively correlated with change in pumpkin intake (r = 0.49; p < 0.001) and change in zucchini intake (r = 0.23; p = 0.03); Children aged 2 and older increased white radish intake more than children younger than 2 (r = 0.25; p = 0.02); Positive correlation between number of times child tasted white radish during intervention and change in radish intake (r = 0.24; p < 0.02); no correlation between number of times child tasted pumpkin or zucchini and change in intake; The number of times zucchini was served to child during intervention was negatively related to change in intake (r = − 0.20; p = 0.04), but not pumpkin or radish; [underlined: Willingness to taste, baseline to post-intervention]; Positive effect of intervention for pumpkin (X2 (2) = 8.37; p =0.02)↑ and white radish (X2 (2) = 10.04; p= 0.006)↑; Pumpkin: ↑ WTT for intervention; ↓ WTT for control group White radish: ↑ WTT for intervention; ↓ WTT for control group ND in WTT for zucchini; Tendency for intervention group to show similar patterns across vegetables (53% of children who increased willingness to taste pumpkin also increased willingness to taste white radish); Model adjustments: none; Funding source(s): The Fresh Produce Centre and the Ministry of Economic Affairs
[underlined: Anzman-Frasca, 2012]^22^; RCT, parallel design (study 1) & NRCT, within subjects (study 2), U.S.; Baseline N= 47 (study 1), 64 (study 2); Analytic N= 41 (study 1), 43 (study 2); Power analysis: NR; Child characteristics (study 1):; - Age: 4.7 ± 0.8 y (3-6 y); - Female: 51%; - Race/ethnicity: 83% white, 10% Asian, 7% other; Child characteristics (study 2):; - Age: 4.4 ± 0.8 y (3-6 y); - Female: 39%; - Race/ethnicity: 80% white, 15% Asian, 5% other; Caregiver characteristics (study 1):; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: median education= bachelor’s degree; most parents employed; 88% parents were married; 89% of families had annual household income >$60,000; Caregiver characteristics (study 2):; - Age: NR; - Female: NR; - Race/Ethnicity: NR; - SEP: median education = master’s degree; most currently employed; 91% married, 77% of families reported income >$60,000; Setting: childcare centers; Study objective and primary outcomes: To compare the effects of flavor–flavor associative conditioning and mere repeated exposure on the liking of vegetables using 2 experiments: a betweensubjects experiment and a withinsubjects experiment. Authors also obtained information on how many tasting trials were needed to produce significant increases in liking under these conditions.; Primary outcomes: Vegetable liking and intake | Target food/ Test Foods (study 1): red bell pepper or yellow squash; disliked vegetables. Dips (for associative conditioning): ketchup, ranch-flavored, cinnamon-sugar.; Target food/ Test Foods (study 2): red bell pepper, yellow squash, sugar snap peas, broccoli, cauliflower; target = 2 disliked vegetables. Dips (for associative conditioning): ketchup, ranchflavored, cinnamon-sugar; Repeated exposure (study 1 &2): Taste; 2x/wk; 4 weeks; 9 exposures (study 1); 8 exposures (study 2); Study 1: classrooms randomly assigned to 1 of 2 vegetables; children randomly assigned to RE or AC intervention. Children asked 2/wk to taste very small portion (~4g) of assigned vegetable in assigned condition. Tastings occurred ~1hr prior to lunch being served.; Intervention/control groups (study 1):; - Repeated Exposure (RE; vegetable alone): children tasted small portion of vegetable without any dip, n=NR; - Associative Conditioning (AC; vegetable + dip): Children tasted small portion of vegetable with dip they selected as “yummiest”, n=NR; Intervention/ control groups (study 2):; - 1 vegetable randomly assigned to either RE or AC treatment. Each child experienced both conditions. Children selected their preferred dip for the AC treatment. The order in which the vegetables were served (RE vs. AC) were counterbalanced between tastings, n= 43; Outcomes and assessment methods:; - Weighed intake, liking assessed using hedonic 3-point scale with cartoon drawings of facial expressions. Vegetables served in their assigned conditions (alone in RE and with dip in AC; study 1). Vegetables served alone for both conditions (study 2).; - Assessment timing: Baseline and Post-Intervention (week 8). Follow-up, week 12 (study 1). | [underlined: Liking, pre- to post-test, study 1]; Assigned vegetable: [OR=5.07; CI: 2.30,11.14; P<0.0001] ↑; Unassigned vegetable: [OR=0.98; CI: 0.55, 1.76; P=0.95]; ND treatment (RE vs. AC); No interaction between time and treatment.; [underlined: Intake, pre- to post-test, study 1]; Change in intake, from pretest, (M=15.4) to post-test (M = 32.6 g) both groups, P<0.01 ↑; ND treatment, (RE vs. AC); Pre-test intake AC vs. RE, P<0.05 ↑; Post-test intake AC vs RE, ND; [underlined: Liking, changes across tasting trials, study 1]; Main effect of time, P<0.01; Main effect of treatment, P<0.05; AC vs. RE [OR= 3.476; CI: 1.32, 9.13]; No interaction between time and treatment; Tasting #1 vs tasting #4 [OR=3.40; CI: 1.63, 7.11; P<0.01]; Tasting #1 vs post-intervention [OR=2.75; CI: 1.38, 5.46, P<0.01]; Tasting #1 vs follow-up [OR= 2.80; CI: 1.27, 6.19; P<0.05]; Tasting #4 vs post-intervention, ND; Tasting #4 vs. follow-up, ND; [underlined: Liking, pre-to post-test, study 2]; (Data reported graphically); [OR= 5.06; CI [ 2.73, 9.39; p<0.0001] ↑; ND treatment (RE vs. AC); No interaction between time and treatment; [underlined: Liking, changes across tasting trials, study 2]; Main effect of time, P<0.01; Main effect of treatment, P<0.01; AC vs RE [OR=1.72; CI: 1.05, 2.81; P<0.05)↑; No interaction between time and treatment; Pre-test vs. Tasting #1 [OR=0.45; CI:0.25, 0.83; P<0.05]; Tasting #1 vs. #4 [OR=1.85; CI:1.17, 2.95; P<0.01]; Tasting #1 vs. post-intervention [OR=1.83, CI:1.02, 3.28; P<0.05]; ND #4 vs. post-intervention; Model adjustments: initial liking of the assigned vs. unassigned vegetable (liking; study 1); age and BMI tested as covariates but did not affect results.; Funding source(s): USDA AFRI
[underlined: Corsini, 2013]^26^; RCT, parallel design, Australia; Baseline N=188; Analytic N= 144; Power analysis: N=52 based on power (0.8) and effect size (0.25) (underpowered); Child characteristics:; - Age: 5.16 ± 0.84 y (4-6 y); - Female: 40%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: 39.1 ± 4.91 y; - Female: 93%; - Race/ethnicity: NR; - Education: 17% High school or less, 20% Technical certificate, 61% University; Setting: Homes; data collected carried out by market research company (fieldworkers experienced working with children and collecting data in homes; children assessed by same fieldworker throughout study); Study objective and primary outcomes: To examine whether parents offering a sticker reward to their child to taste a vegetable the child does not currently consume is associated with improvements in children’s liking and consumption of the vegetable compared with repeated exposure alone. Primary outcome: intake and liking. | Target food/ Test Foods: vegetable ranked 4^th^ by child in forced-choice elimination of least liked.; Repeated exposure: Taste; 1/d; 2 wks; 9 exposures (chosen for analysis); Parents present and ask child to taste target vegetable every day for 2 weeks. Parents asked to prepare vegetable in same manner and at predictable time (before meal or snack) when child would be hungry. Parents could prepare vegetable in usual way (raw or cooked) and were instructed to provide ½ cup portions in bite sized pieces. Addition of oil or butter was permitted but sauces/herbs/spices were discouraged. Parents given instructions for how to respond to refusal (stop after 2 refusals); Intervention/control groups:; - Exposure only (EO): Parents present target vegetable every day for 2 weeks, n=35; - Exposure + Reward (ER): Parents present target vegetable every day for 2 weeks and offered child sticker (‘yummy’, ‘just okay’, ‘yucky’) as reward for tasting vegetable, n=45; - Control: Parents did not receive standardized instruction booklet. Parents asked to maintain normal feeding routines for duration of study, n=64; Outcomes and assessment methods:; - Weighed intake, liking: child rating using 3-point visual ‘faces’ scale.; - Assessment timing: baseline, 2 weeks from baseline (post-intervention), 4 weeks from baseline (follow-up 1) and 3 mo from baseline (follow-up 2). | [underlined: Intake, baseline to post-intervention, group differences]; Significant effect of time on target vegetable intake (χ^2^(1)=22.98, P<0.001); for all 3 groups↑; Significant group-by-time interaction (χ^2^(4)=14.88, P=0.005) ER ↑ target vegetable consumption post-intervention to 3 mo (change 6.47, SE 2.26, P=0.013) and 4 weeks to 3 mo (change 7.23, SE 1.49, P<0.001); Control group ↑ target vegetable consumption post-intervention and 3 mo change (P=0.012); [underlined: Liking, baseline to post-intervention, group differences]; Significant group-by-time interaction on liking from baseline to post-intervention (P=0.029); Increased liking baseline to post-intervention for EO (change 0.48, SE 0.15, P=0.002)↑ and ER (change 0.58, SE 0.13, P<0.001)↑; ND in intake for control; Post-intervention liking ratings for EO and ER significantly higher than for control (P=0.04, P=0.02) but not different from each other; ND in change in liking from post-intervention to 4-week follow-up and 3-month follow-up; Baseline target vegetable liking was significantly lower in children with fewer than 9 tastes (mean −0.63, SD=-0.97), than in children with none or more tastes (mean −0.19, SD= 0.78) (P=0.01); Model adjustments: child’s age; Funding source(s): Horticulture Australia Limited and the Australian Government
[underlined: de Wild, 2017]^28^; RCT, parallel design, Netherlands; Baseline N= 104; Analytic N= 103; Power analysis: N=25 based on power (0.8) and alpha set at (0.05); Child characteristics:; - Age: 35.5 ± 6.8 mo (2-4 y); - Female: 47.6%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: NR; - Race/ethnicity: NR; - SEP: NR; Setting: Home (testing at day-care centers); Study objective and primary outcomes: To investigate the efficacy of offering vegetables prepared in different ways to improve preference for and intake of the vegetable in preschool-aged children. Primary outcome: intake and preference of spinach | Target food/ Test Foods: cooked spinach; generally disliked; Repeated exposure: Taste; 1/wk; 6 wk; 6 exposures; Children served vegetable products (1x/week) at main meal in the evening (home exposure). Families received weekly vegetable parcel with vegetable product for 1 meal, cooking instructions and food diary.; Intervention/control groups:; - Plain spinach (pure): (6 weeks) 50 g plain cooked spinach offered with main evening meal 1/wk, n=26; - Creamed spinach (diluted: (6 weeks) 50 g creamed spinach (plain spinach diluted with cream) offered with main evening meal 1/wk, n=25; - Spinach ravioli (hidden) (6 weeks) 3 pieces ravioli spinach (plain spinach offered in envelope of pasta, each ravioli contained 70% spinach to meet RDA) offered with main evening meal 1/wk, n=26; - Green beans (control) (6 weeks) 50 g green bean offered with main evening meal 1/wk, n=26; *Spinach used for pre-, and post-test was plain cooked spinach (98% frozen chopped spinach) with small amounts of sunflower oil (0.6%), salt (0.1%), and rice flour (1%) to increase children’s willingness to taste; ad libitum intake measured by offering 200g of plain spinach (served warm).; Outcomes and assessment methods:; - Weighed intake, preference, paired preference test with spinach and green beans offered in counterbalanced order; - Assessment timing: pre-test and post-test (1 week after intervention) | [underlined: Intake, group comparisons]; Significant main effect of time: (P=0.001); No main effect of group, no interaction effect; Spinach intake ↑ in all 4 groups (53.4± 56.7 g to 90.6±75.0 g); (means and SD for intervention groups presented graphically); [underlined: Preferences. group comparisons]; Significant effect of group on liking (P=0.005); lower liking scores in spinach ravioli group compared with other groups: 4.5±2.2 vs. 5.6±2.1 (plain spinach), 6.1±1.4 (creamed spinach), and 6.2±1.3 (control); Model adjustments: food neophobia, spinach liking scores, spinach exposure and spinach consumption before the intervention (group effects analysis; Funding source(s): European Community’s Seventh Framework Programme (FP7/ 2007-2013) under grant agreement no. 245012-HabEat
[underlined: Wardle, 2003]^38^; Parallel RCT, U.K.; Baseline N=156; Analytic N=126; Power analysis: NR; Child characteristics:; - Age: 53.2 ± 9.4 mo (2-6 y); - Female: 44.2%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: 36.4 ± 4.7 y; - Female: 95%; - Race/ethnicity: 74% white/Caucasian; - SEP: 68% left full-time education at age of 21; Setting: Home; Study objective and primary outcomes: To evaluate the effectiveness of an exposure-based intervention, carried out by parents in the home, in increasing children’s liking for a previously disliked vegetable. Primary outcome: liking and intake. | Target food/ Test Foods: Target food selected by parent, moderately low ranking (ranking 3) from preference test of 6 test vegetables. Test foods: carrot, celery, tomato, red pepper, green pepper, and cucumber.; Repeated exposure: Taste; 1/d; 14 days; 10 exposures; Parents offered taste of target vegetable every day for 14 days. Importance of not offering a reward was stressed but parents could encourage tasting with modeling or verbal instruction.; Intervention /control groups:; - Exposure: parents offered child taste of target vegetable 1/d for 14 days, n=50; - Information: parents given nutritional advice (5- a-day) and a leaflet for increasing children’s fruit and vegetable intake, n=48; - Control: parents received no further information, n=45; Outcomes and assessment methods:; - Weighed intake; Liking: child rating using hedonic 3-point ‘faces’ scale. Within each category (like, neutral, dislike) preferences were assessed using forced choice elimination (reliability previously demonstrated).; - Assessment timing: baseline and post-intervention | [underlined: Intake, baseline vs. post-intervention, (g) Mean (SEM)]; Exposure group, information group and control group: 4.1 (1.4) vs. 9.0 (1.7); 5.7 (2.1) vs. 7.3 (1.8); 5.7 (1.5) vs. 7.7 (1.6); Significant group x time interaction, p<0.05; Exposure group intake t(33)=4.36, p<0.001 ↑; Information group, NS; control group, NS; [underlined: Willingness to eat (voluntarily ate target vegetable]); Exposure group, Z = 3:16; p < 0.01; Information group, Z = 1:61, NS; and control group, Z = 0:775, NS; Analysis including children who failed to achieve 10 exposures; Group X time interaction: p=0:07; [underlined: Liking, group comparisons]; Rated liking from baseline to post-intervention, p<0.001 ↑; Significant group x time interaction, p<0.001; Rated liking in Exposure group (t(33)=6.64, P<0.001)↑Control group (t(43)==4.19, p<0.001)↑; Information group, NS; Changes in rated liking scores: exposure group vs. information group (p<0.001)↑; exposure vs. Control group (p<0.05)↑; information and control groups (P=0.07); [underlined: Ranked preferences, group comparisons]; Overall sample: target vegetable ranking, post-intervention vs. baseline, p<0.001↑; Group X time interaction on preference ranking p<0.05; Exposure group (P<0.01) and Control group (P<0.05) rated target vegetable significantly higher at second visit; Exposure group (30%) ranked target vegetable as most liked (vs. 5% in control group and 2% in information group; p<0.001); Model adjustments: data for intake were transformed (1/χ + 1) due to strong positive skew.; Funding source(s): Cancer Research U.K.
[underlined: Masento, 2022]^40^; NRCT (matched design), U.K.; Baseline: N=36; Analytical: N=30; Power Analysis: power level 0.80 for 2x2 repeated ANOVA estimated sample n=52 (WTT and liking) and n=200 (intake); Child Characteristics:; - Age: 30.8 ± 9.3 mo (18-48 mo); - Female: 41.7%; - Race/Ethnicity: 91.7 % English, 2.8% White and Asian, 2.8% White-Other, 2.8% NR; Caregiver Characteristics:; - Female: 97%; - Age: NR; - Race/ethnicity: NR; - Parent 1 Education: 2.8% GCSE or equivalent, 8.3% vocational qualification, 2.8% A-level or equivalent, 33.3% Bachelor’s or equivalent, 52.8% Higher degree or equivalent; - Parent 2 Education: 2.8% GCSE or equivalent, 11.1% vocational qualification, 16.7% A-level or equivalent, 38.9% Bachelor’s or equivalent, 27.8% Higher degree or equivalent, 2.8 not reported; Setting: Home; Study objective and primary outcomes: To examine whether looking at a vegetable e-book for a 2-week period accepted preschool children’s acceptance of a target vegetable. Primary outcomes: intake, liking, willingness to taste. | Target food/ test food: 1 of 2 vegetables selected by parent (from list of 24 options); familiar and disliked.; Repeated Exposure: non-taste; 1/d, 2 weeks, 14 exposures; Parent looked at eBook about chosen target vegetable with their child for a few minutes a day every day. At the end of the 2-wk intervention, parents were asked to offer target vegetable and control vegetable (if they hadn’t already during intervention); Intervention/ control groups; Parents selected 2 vegetables from list, 1 was randomly selected as target vegetable and the other was designated as control. At the end of the 2-wk intervention, parents were asked to offer target vegetable and control vegetable (if they hadn’t already during intervention) and complete post-intervention questionnaire.; Outcomes and assessment methods:; - Intake: food frequency past 2 weeks (adapted short form of child food frequency questionnaire, 5-point likert scale, portion size (5-point likert scale); willingness to taste: parent-report measures of willingness to taste (6-point likert scale); liking (6-point likert scale); - Assessment timing: baseline, post-intervention (2 weeks) | [underlined: Intake, portion size]; Main effect of condition, p = 0.04, ηp 2 = 0.14; Main effect of time, p < 0.001, ηp 2 = 0.50; Interaction effect (condition by time), p <0 .001, ηp 2 = 0.349; portion size consumed, pre and post intervention, target vegetable, (Z = −4.41, p < 0.001)↑; portion size consumed, pre and post intervention, control vegetable, ND (Z = −1.39, p = 0.16); portion size consumed, pre intervention, target and control vegetables, ND (Z = −1.58, p = .11),; portion size consumed, post-intervention, target vs. control vegetable, (Z = 2.95, p = 0.003) ↑; [underlined: Intake, frequency of consumption]; Main effect of condition, p = 0.01, ηp 2 = 0.201; Main effect of time, p < 0.001, ηp 2 = 0.391; Interaction effect (condition by time), p =0 .001, ηp 2 = 0.31; Frequency of consumption, pre and post intervention, target vegetable (Z = −3.81, p < 0.001)↑; Frequency of consumption, pre and post intervention, control, ND (Z = −1.18, p = 0.24); Frequency of consumption, target vs. control vegetable, pre-intervention, ND (Z = −0.59, p = 0.055),; Frequency of consumption, target vs. control vegetable, post-intervention (Z = −3.35, p = 0.001)↑; [underlined: Liking]; Main effect of condition, p = 0.021, ηp 2 = 0.171; Main effect of time, p < 0.001, ηp 2 = 0.448; Interaction effect (condition by time), p < 0.05, ηp 2 = 0.231; Liking of target vegetable, pre and post intervention, (Z = −4.14, p < 0.001)↑; Liking of control, pre and post intervention, (Z = −2.34, p = 0.02)↑; Liking of target vs. control vegetable, pre-intervention, ND (Z = −0.25, p = 0.79); Liking of target vs. control vegetable post-intervention, (Z = −2.58, p = 0.01)↑; [underlined: Willingness to taste (WTT)]; main effect of condition, p = .032, ηp2 = 0.15; main effect of time, p = 0.002, ηp2 = 0.30; Interaction effect (condition by time) not significant, p = .098, ηp2 = 0.092; WTT, pre and post rating for target variable (Z = −3.51, p < 0.001) ↑; WTT, pre and post rating for control vegetable, ND (Z = −1.85, p = 0.06); WTT, pre intervention, target vs. control vegetable ND (Z = −1.25, p = 0.21), WTT, post-intervention, target vs. control vegetable, (Z = −2.42, p = 0.02) ↑(data presented graphically); *no correlation between child age and any measure of pre-to-post intervention change; Model Adjustment: none; Funding source(s): European Institute of Innovation and Technology (EIT) Food
[underlined: Ramsay, 2017]^41^; Within-person quasi-experimental, U.S.; Baseline N=33; Analytic N=29; Power analysis: post-hoc based-on acti data suggested at least 10 bet participants were sufficient to phr determine baseline difference on exposures for intake of 90% or greater; Child characteristics:; - Age: 50.7 ± 6.4 mo (3-6 y); - Female: 55%; - Race/ethnicity: NR; Caregiver characteristics:; - Age: NR; - Female: 76%; - Race/ethnicity: 81% Caucasian; - SEP: 88% 4-year degree or higher; 97% two-parent households; 97% working; Setting: Child-care centers; Study objective and primary outcomes: To determine if intake and liking increased with: 1) repeated taste exposure, and 2) pairing repeated taste exposure with developmentally appropriate nutrition phrases: Primary outcomes: intake (g) and liking | Target food/ Test Foods: Lentils; unfamiliar; Repeated exposure: Taste; 1/d; 2-3/wk; 13 wk; 12 exposures; Trained research assistants performed tasting activities between breakfast and lunch and between lunch and afternoon snack. Nutrition phrases highlighted the health benefits of lentils in developmentally appropriate verbiage (e.g., “Lentils help you grow. They give you energy so you can jump high and run fast”); Dry green lentils boiled with water, cooled in refrigerator overnight. Portions of 24.4±0.4g offered at each exposure and tasting activity. Larger portions were offered at baseline and final activities.; Intervention /control groups:; - Repeated Exposure (RE): children completing tasting activities with lentils individually for 13 weeks, n=16; - Repeated Exposure + Nutrition phrases (RE+ CCNP): Children completed tasting activity with lentils individually and received 3 standardized messaged about lentils at specific pointes interspersed during the 14 tasting activities (beginning, middle, end), n=13; Outcomes and assessment methods:; - Weighed intake (g) using pre- and postweights (proportions tasted was calculated by weight eaten divided by weight offered). Lentil liking: lentil preference rankings (hedonic faces, 3-point scale); Assessment timing: baseline, each exposure, post-intervention | [underlined: Intake of lentils, (proportions eaten), Baseline vs. final, g]; RE: 5.2 ± 14 vs. 38.9 ± 49.0;; RE + CCNP: 8.1 ± 15.1 g vs. 57.7 ± 58.0; [underlined: Intake of lentils (proportions eaten), Group comparisons]; Lentil consumption increased for all participants baseline vs. final exposure, 6.5 ± 14.3 g vs 47.3 ± 53.1 g; Proportion of lentils eaten by subgroup (baseline vs. final exposures, estimated Mean, SEM): RE 0.03 (0.02) vs. 0.33 (0.09); RE + CCNP 0.05 (0.02) vs. 0.41 (0.11); No significant main effect of group or group by exposure interaction on proportion of lentils consumed; Main effect of exposure on proportional intake of lentils, p < 0.0001; (DF = 1; n = 29); Main effect of group, p = 0.39; Group by exposure interaction, p = 0.95; [underlined: Liking, group comparisons]; Significant effect of interaction (group x exposure) on children’s liking, χ2 = 5.92; p = 0.05; (DF = 2; n = 25); Liking from baseline to final exposure: RE+CCNP ↑ (33% vs. 62%); RE condition ↓ (50% vs. 42%); Odds of ranking lentils as “yummy” between groups at final exposure, ND; Model adjustments: children’s hunger; Funding source(s): Not reported

a Abbreviations: RCT: Randomized controlled trial; NRCT: non-randomized controlled trial; SEP: Socioeconomic position; g: grams; d: day; wk: week; NR: Not reported; ND: No difference

Table 18 Risk of bias for parallel randomized controlled trials examining repeated exposure to food and food acceptance by children (2-6 years)^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Corsini, 2013^26^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
de Wild, 2017^28^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Wardle, 2003^38^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Anzman-Frasca, 2012^22^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898 31462531 .

Table 19 Risk of bias for cluster randomized controlled trials examining repeated exposure to food and food acceptance by children (2-6 years)^a^

Article | Randomization | Timing of identification and recruitment of individual participants in relation to timing of randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Coulthard, 2018^27^ | LOW | LOW | NOT APPLICABLE | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Hoppu, 2015^31^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Karagiannaki, 2021^32^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Karagiannaki, 2021^33^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
O’Connell, 2012^25^ | SOME CONCERNS | LOW | LOW | NOT APPLICABL E | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Nekitsing, 2019^35^ | LOW | LOW | NOT APPLICABLE | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Nekitsing, 2019^34^ | LOW | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
van Belkom, 2023^36^ | LOW | LOW | NOT APPLICABLE | LOW | LOW | LOW | LOW | LOW
Vandeweghe, 2018^37^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zeinstra, 2018^39^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Byrne, 2002^24^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Holley, 2015^30^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hausner, 2012^29^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Anzman-Frasca, 2012^22^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Bouhlal, 2014^23^ | SOME CONCERNS | LOW | NOT APPLICABLE | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898 31462531 .

Table 20 Risk of bias for non-randomized controlled trials examining repeated exposure to food and food acceptance by children (2-6 years)^a^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Masento, 2023^40^ | MODERATE | MODERATE | LOW | MODERATE | MODERATE | SERIOUS | LOW | SERIOUS
Ramsay, 2017^41^ | MODERATE | LOW | LOW | LOW | LOW | LOW | LOW | MODERATE

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )