# Results

## Literature search and screening results

The literature search (Appendix 4) yielded 10150 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 9460 titles, 589 abstracts, and 80 full-texts articles. Reasons for full-text exclusion are in Appendix 5. Fourteen additional articles were identified from the existing systematic review, and 6 additional articles were identified from the manual search. The body of evidence included 41 articles:

- Infants and young children (birth to 24 months) were examined in 21 articles
- Children (2 to 6 years) were examined in 20 articles

Figure 2 Literature search and screen flowchart

P489#yIS1

## Infants and young children (birth to 24 months)

### Description of the Evidence

#### Design

The body of evidence on repeated exposure to a food(s) by infants and young children and food acceptance includes 21 articles (19 independent studies) from 16 randomized controlled trials (RCT),^1–18^ and 3 non-randomized controlled studies (NRCT).^19–21^ Sample sizes ranged from 20 participants^21^ to 267 participants.^4^ Eight studies had less than 50 participants,^1,9,10,12,18–21^ 9 studies had 50 to 100 participants,^2,3,5–7,11,13–15,17^ and 3 studies had more than 100 participants (Table 13).^4,8,16^

##### Setting

While the majority of studies were conducted in a home setting (and tested food acceptance in a lab),^2,3,6–21^ some took place in a daycare or preschool.^1,4,5,7^

##### Foods

###### Types of foods

The RCTs were designed to investigate repeated exposure to a target food on acceptance of the same food or other foods varying in their similarity to the target food (e.g., other vegetable or fruit). Twelve studies tested repeated taste exposure of only a vegetable or multiple vegetables,^1,4–6,8,10–12,16–18,20^ and 7 studies tested repeated taste exposure to both vegetables and fruits.^2,3,7,9,13–15,19,21^ No articles assessed repeated exposure to only fruits. The target vegetables included green beans, peas, squash, carrots, artichoke, celeriac, swede, turnip, spinach, broccoli and a disliked vegetable (determined by parent). The most commonly included target vegetable was green beans.^2,3,9,12,14,16,18^ The target fruits included plum, banana, apple, peach, prune, and pear. Banana was the most commonly used target fruit.^2,3,19^

With the exception of Forestell and Mennella^9^ and Mennella et al.^14^ a single vegetable or fruit was served alone at an eating occasion and the type of vegetable or fruit varied across eating occasions, with 1 eating occasion per day at the same time each day. In the study by Forestell and Mennella,^9^ green beans were served first, followed by peaches within 1 hour, and in Mennella et al.^14^ 1 group of infants received 2 vegetables (spinach or peas and squash or carrots) per eating occasion.

###### Familiarity

Fifteen of 19 studies reported on children’s initial familiarity to the target vegetable or fruit.^1–7,10–13,15,18–21^ Familiarity refers to the experience a child has with the food being offered before the repeated exposure intervention. Ten studies investigated repeated taste exposure to a novel vegetable or fruit^1,4,6–8,10,11,18,19,21^ and 7 studies investigated repeated taste exposure to a familiar food.^2,3,5,11–13,15,20,21^ Of the 7 studies that included a familiar target food, 4 studies described the target vegetable or fruit as initially disliked^11–13,15,20^ while 2 referred to the foods as less commonly consumed/ low consumption.^2,3,5^ Of the articles that did not report on familiarity to the target food, 5 studies included children early in the complementary feeding period (mean age around 6 months) for whom foods were likely unfamiliar or less commonly consumed.^6,9,14,16,17^

###### Amount, timing, preparation

Most studies assessed repeated taste exposure to food in the form of purées. Parents were provided with portions ranging from 50-226 g during the repeated taste exposure intervention with 6 studies reporting the offered amount ranging from 71-110 g,^1,10,12,14,17,18^ and 7 studies reporting the offered amount ranging from 125-226g.^2,3,5,6,8,9,19,20^ Most studies instructed the caregiver to feed the puréed target food during their usual meal or snack time, at their customary pace, and continue feeding until the infant rejected the food more than 3 consecutive times. In some studies caregivers were instructed to feed as much or as little as the infant liked and second pot of food was offered if the first pot was completely consumed.^1,5,9,20^ Most studies also instructed caregivers to refrain from introducing a new food during the intervention period. Of the 14 studies that offered purées, 10 used commercially available purées,^2,3,8–10,12,14,16,18–20^ 3 used laboratory-made purées,^1,5,6^ and Remy et al.^17^ used both laboratory-made and commercially available purées. Birch et al.^19^ also tested acceptance of a homemade purée following repeated taste exposure to a commercial purée product.

#### Repeated exposure interventions

##### Number, frequency, duration

The total number of repeated exposures to foods ranged from 6 times^1,4,16^ to 15 times,^11,13,15^ with a frequency of exposures that ranged from 1 time per day to 2-3 times per week^1,17^; however, the majority of studies tested 1 exposure per day.^5,6,8–21^ The total duration of studies ranged from 8 days^9,14^ to 28 days.^7,16^ Repeated exposure to a single food frequently occurred on 8 to 16 consecutive days,^5,6,9,10,14,17–20^ while exposure to multiple fruits and/or vegetables frequently occurred every second, third or fourth day over a period of 2 to 4 weeks.^1–3,7,12,14,20,21^ Less frequently, exposure to multiple vegetables were planned so children were exposed to an individual vegetable for 5 or 6 consecutive days according to a cycle that occurred over a 2-to-4-week period.^8,17^

##### Type of exposure

Of the 19 studies, 14 (12 RCTs and 2 NRCT) examined repeated taste exposures to a single vegetable or fruit^5,6,9,10,14,16–19^ or multiple vegetables or fruits.^1–3,6,8,9,12,14,20^ Three studies (2 RCT and 1 NRCT) examined the effects of non-taste exposure to fruits and/or vegetables.^7,11,21^ Non-taste sensory intervention included sensory exposure that included sight, sound, smell and touch,^7^ and visual exposure to the picture of target fruits and vegetables in a storybook.^11,21^ Three articles from 2 RCTs examined the combined effects of both repeated taste and non-taste exposure to multiple novel vegetables^4^ and taste and non-taste exposure of a single disliked fruit and vegetable on food acceptance.^13,15^ The non-taste component for 1 study included weekly sensory lessons around taste and the 5 senses (taste, smell, sight and color, touch, and sound) for 3 days per week for 3 months.^4^ The other study used visualization to a picture of either a target fruit or vegetable via story book for a period of 2 weeks in combination with repeated taste exposure to the target fruit or vegetable.^13,15^

#### Study population

Nine studies were conducted in the U.K.,^1,5–7,11–13,15,21^ 6 studies were conducted in the U.S.,^9,10,14,16,18,19^ and 1 study was conducted in each of the following countries: France,^17^ Germany,^20^ Netherlands,^2,3^ and Norway.^4^ One study included populations from the U.K, Greece, and Portugal.^8^

Subject characteristics, namely child’s age and sex, were well distributed within the body of evidence. Mean age of participants at the start of the study ranged from 22 weeks^18^ to 24 months.^5^ Two studies did not provide a mean, but the subject age ranged from 15 to 56 months^1^ and birth to 2 years.^7^ The repeated taste exposure component of the Paul et al.^16^ study occurred after parents reported that their infants were ready to begin consuming solids, at least 4 months of age; however, the authors didn’t indicate the mean age at the time of the repeated exposure assessment. Studies with children older than 24 months were included in the body of evidence if they provided subgroup analyses looking specifically at infants and young children within the birth to 24-month age range,^1,5^ otherwise they were excluded. All but 2 articles reported sex,^1,7^ and girls and boys were fairly equally represented, ranging from 40% female^17^ to around 58% female.^18^

In most studies caregivers were comprised of 100% mothers.^6,8–10,16,18,20,21^ Seven articles reported race and ethnicity for mothers and/or infants.^9–11,13–16^ Of these, 4 studies included data from mostly (>80%) white participants^11,13,15,16^ and 3 studies included data from diverse racial/ethnic backgrounds.^9,10,14^ Samples in these studies ranged from 29.7-45.8% white, 10-55.4% black, 2.1-27% Hispanic, and 1.5-11.4% other/mixed race.^9,10,16^ One study described participant recruitment as occurring in an inner-city area with diverse ethnic and social groups.^6^ Results do not seem to vary between studies with predominantly White samples compared with studies that included more mixed racial/ethnic groups; however, no study performed analysis based on race or ethnicity.

A variety of measures of socioeconomic position (SEP; e.g., parental education, household income) were reported in 11 studies.^2,4,8,9,11–13,15,16,19,20^ Parent education was described as low/middle/high,^2^ highest degree achieved,^8,16,20^ mean years of schooling,^9,19^ and percent of mothers/fathers with a University degree.^4,11–13,15^ Household income was described in terms of income brackets^16^ and percent of families earning greater than £50,000 per year.^13,15^ Two studies had information about participation in food assistance programs among participants, namely the Special Supplemental Nutrition Program for Women, Infants, and Children (WIC).^9,15^ In these studies, participants in WIC ranged from around 44%^9^ to 100%.^14^ The inconsistencies between reporting make it difficult to draw conclusions about who was represented in the studies and the effects of repeated exposure on food acceptance by SEP.

#### Outcomes

Food acceptance was indicated by a positive change to 1 of the following outcomes: food intake,^1–21^ duration of feed,^10,14^ rate of feeding,^9,10,12,14^ parent or researcher perceived liking,^2,3,8–10,12–15,17,18,20^ willingness to taste,^7,11,13,21^ or facial and/or body response indicating liking.^9^ Intake was assessed using weighed intake in most studies,^4,15^ food frequency questionnaire in 2 studies,^4,15^ and mean intake of child-sized portion on a scale from 0 to 4 in 1 study.^13^ Rate of feed and duration of feeding was assessed using video recorded feeding episodes by blinded experimenter.^9,10,12,14^ Liking was typically assessed as perceived liking using parent and/or experimenter ratings on a scale.^2,3,8–10,12–15,17,18,20^ Willingness to taste included experimenter reported whether food was touched and tasted and in which order^7,11,21^ and mean proportions of offers tasted.^13^ Table 5 indicates the food acceptance measures examined by included studies and exposure type.

Table 5 Food acceptance outcome indicators by study and exposure type by infants and young children (birth to 24 months)

Study | Exposure Type | Intake | Perceived liking | Duration of feed | Rate of feed | Facial/body response | Willingness to taste
6 studies: Ahern, 2014^1^; Birch, 1998^19^; Caton, 2013^5^; Coulthard, 2014^6^; Paul, 2011^16^; Blomkvist, 2021^4^ | 5 Taste 1 Both taste and non-taste | X
6 studies: Barends, 2013^2^ 2014^3^; Fildes, 2015^8^; Maier, 2007^20^; Owen, 2018^15^; Remy, 2013^17^; Sullivan, 1994^18^ | 5 Taste 1 Both taste and non-taste | X | X
1 Study: Houston-Price, 2019 ^13^ | Both taste and non-taste | X | X | | | | X
1 study: Hetherington, 2015 ^12^ | Taste | X | X | | X
2 studies: Gerrish, 2001 ^10^ ; Mennella, 2008 ^14^ | Taste | X | X | X | X
1 study: Forestell, 2007 ^9^ | Taste | X | X | | X | X
1 study: Heath, 2014 ^11^ | Non-taste | X | | | | | X
2 studies: HoustonPrice, 2009 ^21^ ; Dazeley, 2014 ^7^ | Non-taste | | | | | | X
Total: 20 studies | | 18 | 11 | 2 | 4 | 1 | 4

### Conclusion statements and grades: taste exposure

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between repeated exposure to foods and food acceptance?” based on their review of the body of evidence examining repeated taste exposure and food acceptance by infants and young children ages birth to 24 months.

#### Conclusion statement and grade

Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

##### Synthesis of the evidence: repeated taste exposure to a target vegetable and acceptance of a target vegetable

The body of evidence on repeated exposure to a single target vegetable and acceptance of target vegetable by infants and young children includes 13 articles (12 independent studies) from 10 randomized controlled trials^1–3,5,9,10,12,14,16–18^ and 2 non-randomized controlled trials.^19,20^ All studies that tested repeated taste exposure of single vegetable or multiple vegetables showed a positive effect on target vegetable acceptance; 12 of 12 studies showed increased weighed intake,^1–3,5,9,10,12,14,16–20^ 4 of 4 showed an increase in rate of feed,^9,10,12,14^ and 3 of 10 studies showed an increase in perceived liking.^2,3,17,18^

Two studies investigated the effects of repeated taste exposure to multiple vegetables.^2,14^ One study had 2 groups that were exposed to different combinations of vegetables; 1 group was exposed to green beans, broccoli, cauliflower; another group was exposed to artichoke, broccoli, cauliflower.^2^ While the groups exposed to green beans, broccoli and cauliflower had greater intake of green beans after the exposure period, the group exposed to artichoke, broccoli and cauliflower showed no change in intake of artichoke.^2^ One study had 3 groups, 1 group exposed to green beans at target meal, 1 group exposed to squash, spinach, carrot, or pea between meals and the third group exposed to squash, spinach, carrot, or pea between meals and within meals.^14^ While there was no change in intake and rate of feed of green beans in the green beans group, there was an increase in intake and rate of feed of carrot and spinach in the 2 groups exposed to squash, spinach, carrot, or pea.^14^

Barends et al.^2^ showed that 1 of the groups exposed to green beans, broccoli and cauliflower had greater perceived liking of green beans after the exposure period.^2^ Meanwhile, there was no change in intake or perceived liking of artichoke within the group exposed to artichoke, broccoli, and cauliflower.^2^ Additionally, 5 studies also showed no change in perceived liking of target vegetable after the exposure period.^9,10,12,14,20^

In summary, all studies that examined the effects of repeated taste exposure to a single target vegetable showed an overall increase in acceptance of the same vegetable, indicated by at least 1 measure of outcome assessment, primarily increased weighed intake. In addition, all studies that examined the effects of repeated taste exposure to more than 1 target vegetable showed effects on 1 or more of those vegetables.

##### Assessment of the evidence: repeated taste exposure to a target vegetable and acceptance of target vegetable

The body of evidence examining repeated taste exposure to a target vegetable and acceptance of the target vegetable by infants and young children ages birth to 24 months included 13 articles (12 independent studies); 10 RCTs and 2 NRCTs. A moderate grade was assigned to the evidence supporting this conclusion statement. The abundance of RCT designs provided direct evaluation of the association of interest. Results were consistent in direction across studies, with 12 out of 12 studies demonstrating effects of repeated exposure to vegetables to increase 1 or more indicators of food acceptance. The reliance on RCT designs also was considered to afford moderate protections against bias. These strengths were weighed against limitations concerning small sample sizes and the lack of evidence in U.S. population subgroups of diverse race and ethnicity as well as socioeconomic position. Although risk of publication bias is always of potential concern, small studies reporting both significant and null findings were included in this review. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The assessment of each grading element used when considering the strength of the evidence is outlined and described below.

###### Consistency

There were few to no concerns with consistency. Findings are consistent in direction such that there is a positive effect of repeated taste exposure from almost all studies on 1 or more indicators of acceptance. Findings were mostly from randomized controlled trials using a within-subject design testing the effect of repeated taste exposure to vegetables. Weighed food intake and, to a smaller extent, rate of feeding were the predominant means of capturing an increase in acceptance and most studies showed increases in weighed intake and/or rate of feed following repeated exposure to the target vegetable. There was less consistency in the more subjective assessment of parental perception of perceived liking. There were some important methodological differences across studies in terms of the foods provided as well as variations in number, frequency, and duration of repeated exposure.

###### Precision

There were some concerns related to precision due to small sample sizes. Only 1 study reported a priori power analysis and was sufficiently powered.

###### Risk of bias

The risk of bias summary tables (Table 14, Table 15, Table 16) indicated certain areas that may be of concern for internal validity purposes. These included concern for bias in the measurement outcomes associated with perceived liking (due in part to lack of blinding of researchers, outcome assessors, or participants), limited reporting of randomization methods, missing data and lack of evidence for a pre-analysis plan, and not accounting for key confounders for non-randomized control trials. However, it was determined that these were not considered to be significant limitations for the body of evidence given that a good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals:

- Measurement of perceived liking: blinding is not possible in within subjects designs on this topic, given the nature of the exposure. As such, risk for bias may be higher for more subjective assessments of food acceptance such as caregiver ratings of the child’s perceived liking, compared to measures of weighed intake which are more objective. Perceived liking however was only 1 of 6 outcome measures considered and rarely evaluated in the absence of objective measures of intake. Further, caregiver perceptions of liking are important to assess to the extent that such perceptions may influence whether the food is offered. For these reasons, the potential limitations of this subjective measures are unlikely to have significant influence on risk of bias.
- Few studies reported the method for randomization of participants to the intervention and identified a pre-analysis plan. These limitations were considered to reflect standards of reporting at the time the studies were published. A good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals. As such, these limitations were judged to have limited impact of risk of bias.
- Missing data was not adequately described and accounted for numerous analyses.

###### Directness

There were few to no concerns related to directness given that the preponderance of evidence involved RCT designs that were designed to directly examine the effect of repeated exposure on food acceptance by infants and young children ages birth to 24 months.

###### Generalizability

There were significant concerns regarding the lack of diversity in participant race/ethnicity and socio-economic position as well as the generalizability of international studies to the U.S. population. Most participants were from relatively high socioeconomic backgrounds, with little racial/ethnic diversity reported. Lack of information on SEP measures, and lack in standardization of reporting for studies that reported on SEP measures made information on education and income difficult to interpret. The majority of evidence included infants and young children within the U.S. and developed European countries aged 4 to 24 months; however, there are differences with respect to complementary feeding practices, cultural foods, diets, and eating values and norms between countries. This body of evidence is both practically and clinically important to the U.S. population because it addresses the critical issue of introduction of foods and the development of healthy eating habits.

#### Conclusion statement and grade

Repeated taste exposure to a single fruit is likely to increase acceptance of the target fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

##### Synthesis of the evidence: repeated taste exposure to a target fruit and acceptance of a target fruit

The body of evidence on repeated exposure to target fruit and acceptance of target fruit by infants and young children includes 5 articles (4 independent studies) from 3 RCTs^2,3,9,14^ and 1 NRCT.^19^ All 4 studies showed a positive effect on target fruit acceptance at least in 1 measure of acceptance; 3 of 4 studies showed increased weighed intake,^2,3,14,19^ 1 of 2 showed an increase in rate of feed,^9^ and 1 of 3 studies showed an increase in perceived liking.^2,3^

Some studies included repeated exposure to more than 1 target fruit. In Barends et al.^2^ 4 study groups were tested.^2^ The 2 groups that were exposed to different combinations of fruits included group 1 that was exposed to apples, bananas, pears and group 2 that was exposed to plums, bananas, pears.^2^ The group 2 exposed to plums, bananas, and pears had greater intake and perceived liking of plums after the exposure period.^2^ Meanwhile, there was no change in intake or perceived liking of the target fruit (apple) within the group 1 exposed to apples, bananas, and pears. In a follow-up of the same study apple intake was compared between the groups exposed to vegetables and the groups exposed to fruits at 6-month and 12-month follow-up.^3^ Findings showed no differences in intake of apples between vegetable and fruit group at 6-month and 12-month follow-up.^3^ One study found 10 exposures to bananas resulted in a significant increase in weighed intake of bananas pre- to post-intervention, but only in the group exposed to banana and not in the group exposed to banana and peas.^19^ One study found 8 exposures to peaches did not significantly affect intake or perceived liking of peaches, but increased rate of feed; however, peaches were only served to a group that had eaten green beans 1 hour prior to the peach test, which could have influenced subsequent measures of food acceptance.^9^ Mennella et al.^14^ found 8 exposures to pears or a variety of fruits had a positive effect on pear intake in infants, but a null effect on rate and duration of feed as well as perceived liking of pears.

In summary, all of the studies that examined the effects of repeated taste exposure to a single target fruit showed an overall increase in acceptance of the same fruit, indicated by at least 1 measure of outcome assessment, primarily increased weighed intake. Further, 4 of 5 studies that evaluated repeated exposure to more than 1 fruit demonstrated effects on at least 1 or more measures of acceptance among 1 or more of the fruits tested.

##### Assessment of the evidence: repeated taste exposure to a target fruit and acceptance of target fruit

The body of evidence evaluating the effects of repeated taste exposure to a target fruit on acceptance of the target fruit by infants and young children ages birth to 24 months included 5 articles (4 independent studies), 3 RCTs and 1 NRCT. A moderate grade was assigned to the evidence supporting this conclusion statement. The abundance of RCT designs provided direct evaluation of the association of interest. Results were consistent in direction across studies with 4 out of 4 studies demonstrating effects of repeated exposure to fruit to increase 1 or more indicators of food acceptance. The reliance on RCT designs was considered to afford moderate protections against bias. These strengths were weighed against limitations concerning small sample sizes and the lack of evidence in U.S. population subgroups of diverse race and ethnicity as well as socioeconomic position. Although risk of publication bias is always of potential concern, small studies reporting both significant and null findings were included in this review. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The assessment of each grading element used when considering the strength of the evidence is outlined and described below.

###### Consistency

There were few concerns related to consistency. Findings are consistent in direction such that there is a positive effect of repeated taste exposure on at least 1 measure of fruit acceptance. However, there were some inconsistencies within studies that included more than 1 indicator of food acceptance, and the body of evidence investigating repeated taste exposure to fruits was small.

###### Precision

There were concerns due to small sample sizes and concerns that none of the studies reported a priori power analysis.

###### Risk of bias

The risk of bias summary tables (Table 14, Table 15, Table 16) indicated certain areas that may be of concern for internal validity purposes. These included concern for bias in the measurement outcomes associated with perceived liking (due in part to lack of blinding of researchers, outcome assessors, or participants), limited reporting of randomization methods, missing data and lack of evidence for a pre-analysis plan, and not accounting for key confounders for non-randomized control trials. However, it was determined that these were not considered to be significant limitations for the body of evidence given that a good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.

###### Directness

There were few to no concerns related to directness given that the preponderance of evidence involved RCT designs that were designed to directly examine the effect of repeated exposure on food acceptance by infants and young children ages birth to 24 months.

###### Generalizability

There were significant concerns due to a lack of diversity in participant race/ethnicity and socio-economic position as well as generalizability of international studies to the U.S. population. Most participant were from relatively high sociodemographic backgrounds, with little racial/ethnic diversity reported. Lack of information on SEP measures, and lack in standardization of reporting for studies that reported on SEP measures made information on education and income difficult to interpret. The majority of evidence included infants and young children within the U.S. and developed European countries aged 4 to 24 months; however, there are differences with respect to complementary feeding practices, cultural foods, diets, and eating values and norms between countries. This body of evidence is both practically and clinically important to the U.S. population because it addresses the critical issue of introduction of foods and the development of healthy eating habits.

#### Conclusion statement and grade

Repeated taste exposure to a vegetable is likely to increase acceptance of a different vegetable, but not a fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

##### Synthesis of the evidence: repeated taste exposure to a target vegetable and acceptance of a different vegetable or fruit

The body of evidence examining the effects of repeated taste exposure to a target vegetable on acceptance of a different vegetable and fruit include 12 articles (11 independent studies) from 10 RCTs^2,3,5,6,8–10,12,14,17,18^ and 1 NRCT.^19^ Ten studies tested the impact of repeated taste exposure to 1 or more vegetables on a different vegetable,^2,5,6,8,10,12,14,17–19^ and 4 studies examined the impact of repeated taste exposure to 1 or more vegetables on acceptance of a fruit.^2,3,8,19^

Acceptance of different vegetable(s): Of the 10 studies which tested the impact of repeated taste exposure to 1 or more vegetables on a different vegetable,^2,3,5,6,8,10,12,14,17–19^ 6 studies showed that repeated taste exposure to a target vegetable increases intake of a different vegetable,^2,5,6,14,18,19^ however the types of target vegetables differed between studies. One study found that repeated taste exposures to peas led to increased intake of carrots or corn.^19^ One study found that repeated exposures to artichoke (either plain artichoke, sweetened artichoke, or artichoke with added oil) increased intake of carrots.^5^ Coulthard et al.^6^ compared repeated taste exposure to carrots with repeated taste exposure to a variety of vegetables (parsnips, zucchini, and sweet potatoes) on intake of peas.^6^ There was a significant interaction between child age at introduction to solid foods and intervention group such that infants who were introduced to foods after 5.5 months and were exposed to a variety of vegetables consumed more peas than those introduced to foods before 5.5 months and were exposed to a single vegetable.^6^ In Barends et al.^2^ the group of infants repeatedly exposed to green beans increased their intake of artichoke, and the group repeatedly exposed to artichoke increased their intake of green beans.^2^ Similar findings were also found in Sullivan and Birch^18^ for groups exposed to green beans or peas. Mennella et al.^14^ tested repeated taste exposure to a variety of vegetables. Group 1 was offered 1 of 4 vegetables (squash, spinach, peas, and carrots) per day; group 2 was offered 2 of the same 4 vegetables per day (at the same meal).^14^ Group 1 did not increase intake of a different vegetable (green beans), but group 2 increased intake and feeding rate of green beans.^14^

Three studies found no effect of repeated taste exposure to a vegetable or vegetables on acceptance of a different vegetable.^10,12,17^ One study showed no change in intake and rate of feed of carrots after 9 exposures to potatoes.^10^ One study tested the effects of repeated taste exposure to artichoke (plain, sweetened, or energy dense) on acceptance of a carrot.^17^ Repeated taste exposure to artichoke resulted in higher intake of carrots than artichoke in groups exposed to sweetened and energy dense carrots, but not in the group exposed to plain artichoke.^17^ The third study tested the effects of repeated exposure to multiple vegetables (carrots, green beans, spinach, broccoli) on acceptance of parsnip and found no difference in parsnip intake between intervention and control group (no exposure to vegetables).^12^

Acceptance of a fruit: Four studies examined the impact of repeated taste exposure to 1 or more vegetables on acceptance of a fruit and found no effect on fruit acceptance.^2,3,8,9,19^ One study investigated repeated taste exposure to 5 vegetables (vegetables differed among participants) but found no effect on acceptance of a fruit (peaches).^8^ One study examined the effects of repeated taste exposure to a single vegetable (green beans) on intake of a fruit (peaches) and found no effect on intake but an increase in rate of consumption from pre- to post-intervention.^9^ One study investigated repeated taste exposure to multiple vegetables (artichokes, broccoli, cauliflower or green beans, broccoli, cauliflower) on acceptance of a fruit (apples) and found repeated taste exposure to a variety of vegetables had no effect on intake of a fruit.^2,3^ At 6- and 12-month follow-up, there was no difference in intake of a fruit (apple) between the group with repeated taste exposed to apples and the group with repeated taste exposure to a vegetable (green beans, no exposure to apples).^2,3^ The fourth study did not show a change on intake of bananas after repeated taste exposure to peas.^19^ Three of these studies that assessed liking indicated no changes in liking of a fruit after repeated exposure to a vegetable.^2,8,9^

##### Assessment of the evidence: repeated taste exposure to a target vegetable and acceptance of a different vegetable or fruit

The body of evidence examining repeated taste exposure to a target vegetable and acceptance of a different vegetable and fruit by infants and young children ages birth to 24 months included 12 articles (11 independent studies),10 RCTs and 1 NRCT. A moderate grade was assigned to the evidence supporting this conclusion statement. The abundance of RCT designs provided direct evaluation of the association of interest. Results were consistent in direction across studies, with 8 out of 11 studies demonstrating effects of repeated exposure to vegetables to increase 1 or more indicators of food acceptance of a different vegetable. The reliance on RCT designs was also considered to afford moderate protections against bias. These strengths were weighed against limitations concerning small sample sizes and the lack of evidence in U.S. population subgroups of diverse race and ethnicity as well as socioeconomic position. Although risk of publication bias is always of potential concern, small studies reporting both significant and null findings were included in this review. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The assessment of each grading element used when considering the strength of the evidence is outlined and described below.

###### Consistency

There were few concerns related to consistency. Findings are reasonably consistent in direction such that there is a positive effect of repeated taste exposure on 1 or more outcome of interest in 8 out of 11 studies. There were methodological differences that were important to consider when synthesizing the evidence including variations in target and test foods across studies and variations in number, frequency, and duration of exposures.

###### Precision

There were some concerns with precision due to small sample sizes. Only 3 studies reported a priori power analysis and were sufficiently powered.

###### Risk of bias

The risk of bias summary tables (Table 14, Table 15, Table 16) indicated certain areas that may be of concern for internal validity purposes. These included concern for bias in the measurement outcomes associated with perceived liking (due in part to lack of blinding of researchers, outcome assessors, or participants), limited reporting of randomization methods, missing data, and lack of evidence for a pre-analysis plan, and not accounting for key confounders for non-randomized control trials. However, it was determined that these were not considered to be significant limitations for the body of evidence given that a good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.

###### Directness

There were few to no concerns related to directness given that the preponderance of evidence involved RCT designs that were designed to directly examine the effect of repeated exposure on food acceptability by infants and young children ages birth to 24 months.

###### Generalizability

There were significant concerns regarding the lack of diversity in participant race/ethnicity and socio-economic position as well as the generalizability of international studies to the U.S. population; Most participants in the body of evidence were from relatively high socioeconomic backgrounds with little racial/ethnic diversity reported. Lack of information on SEP measures, and lack in standardization of reporting for studies that reported on SEP measures made information on education and income difficult to interpret. The majority of evidence included infants and young children within the U.S. and developed European countries aged 4 to 24 months; however, there are differences with respect to complementary feeding practices, cultural foods, diets, and eating values and norms between countries between countries. This body of evidence is both practically and clinically important to the U.S. population because it addresses the critical issue of introduction of foods and the development of healthy eating habits.

#### Conclusion statement and grade

Repeated taste exposure to a fruit may increase acceptance of a different fruit, but not a vegetable, by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

##### Synthesis of the evidence: repeated taste exposure to a target fruit and acceptance of a different fruit and vegetable

The body of evidence that examined the effects of repeated taste exposure to a target fruit and acceptance of a different fruit and vegetable include 3 articles, 2 RCTs^2,14^ and 1 NRCT.^19^ Three studies that examined the effects of repeated taste exposure on 1 or more fruits and acceptance of a different fruit and the same 3 studies also examined the effects of repeated taste exposure to 1 or more fruits on acceptance of a vegetable.^2,14,19^

Acceptance of different fruit(s): Three studies tested the effect of repeated taste exposure to 1 or more fruits on acceptance of a different and showed increased intake of at least 1 fruit.^2,14,19^ Barends et al.^2^ found that 1 group repeatedly exposed to plums, bananas, and pears increased their intake of a different fruit (apples), but a different group repeatedly exposed to apple, banana and pear did not increase their intake of a different fruit (plum).^2^ Birch et al.^19^ found that repeated taste exposures to bananas led to increased intake of a different fruit, pears, or peaches. Additionally, Mennella et al.^14^ found that repeated taste exposures to peaches, prunes, and apples (1 fruit per day) increased intake of a different fruit (pears) but not rate of feed or duration of feed. Two of these studies also assessed maternal rated liking of a different fruit after repeated taste exposure to target fruits and did not show a change.^2,14^

Acceptance of a vegetable: Of the 3 studies that tested repeated taste exposure to 1 or more fruits on acceptance of a vegetable, none found an increase in intake.^2,14,19^ In Barends et al.^2^ intake of green beans was tested after repeated taste exposure to apple or plum and in Birch et al.^19^ intake of peas was tested after repeated taste exposure to bananas. Mennella et al.^14^ tested intake of green beans following repeated taste exposure to pear or a variety of fruits (peach, prune, and apple) and found no change in intake but did find an increased rate of feed of green beans for both groups exposed to fruits.

Perceived liking rated by mother or researcher also was assessed in 6 studies.^2,8,10,14,17,18^ While 4 studies did not report any change in liking of a different vegetable after repeated exposure to target vegetable or fruit, Fildes et al.^8^ reported an increase in researcher rated liking but not maternal rated liking of a different vegetable.^8,10,14,17^ One study reported increased liking for green beans when infants were exposed to artichokes, but no increase in liking of artichoke when children were exposed to green beans.^2^ The final study reported an increase in liking of a different (non-exposed) vegetable from pre- to post-intervention.^18^

##### Assessment of the evidence: repeated taste exposure to a target fruit and acceptance of a different fruit and vegetable

The body of evidence examining repeated taste exposure to a target fruit and acceptance of a different fruit or vegetable by infants and children ages birth to 24 months included 3 articles, 2 RCTs and 1 NRCT. A limited grade was assigned to the evidence supporting this conclusion statement. The use of RCT designs allowed direct evaluation of the association of interest but there were a small number of studies with inconsistent results. Concerns regarding consistency and lack of generalizability also influenced grading. Although risk of publication bias is always of potential concern, small studies reporting both significant and null findings were included in this review. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The assessment of each grading element used when considering the strength of the evidence is outlined and described below.

###### Consistency

There were concerns related to consistency of reported results. Weighed food intake and perceived liking were the predominant means of capturing an increase in acceptance and there was not good agreement between measures within studies or between studies related to acceptance of the test food. There were also methodological differences that were important to consider when synthesizing the evidence including variations in target and test foods across studies and variations in number, frequency, and duration of exposures.

###### Precision

There were concerns with precision due to small sample sizes and that none of the studies reported a priori power analyses.

###### Risk of bias

The risk of bias summary tables (Table 14, Table 15, Table 16) indicated certain areas that may be of concern for internal validity purposes. These included concern for bias in the measurement outcomes associated with perceived liking (due in part to lack of blinding of researchers, outcome assessors, or participants), limited reporting of randomization methods, missing data, and lack of evidence for a pre-analysis plan, and not accounting for key confounders for non-randomized control trials. However, it was determined that these were not considered to be significant limitations for the body of evidence given that a good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.

###### Directness

There were few to no concerns related to directness given that the preponderance of evidence involved RCT designs that were designed to directly examine the effect of repeated exposure on food acceptability by infants and young children ages birth to 24 months.

###### Generalizability

There were significant concerns regarding the lack of diversity in participant race/ethnicity and socio-economic position as well as the generalizability of international studies to the U.S. population. Most participants in the body of evidence were from relatively high socioeconomic backgrounds with little racial/ethnic diversity reported. Lack of information on health equity components and predominantly White population for the studies that report on race and ethnicity, the findings should be generalized to the U.S. population with caution. Lack in standardization of reporting made information on education and income difficult to interpret. The majority of evidence included infants and young children within the U.S. and developed European countries aged 4 to 24 months; however, there are differences with respect to complementary feeding practices, cultural foods, diets, and eating values and norms between countries. This body of evidence is both practically and clinically important to the U.S. population because it addresses the critical issue of introduction of foods and the development of healthy eating habits.

### Conclusion statement and grade: non-taste exposure

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between repeated exposure to foods and food acceptance?” based on their review of the body of evidence examining repeated non-taste exposure and food acceptance by infants and young children ages birth to 24 months.

#### Conclusion statement and grade

A conclusion statement cannot be drawn about the effect of repeated non-taste exposure, either alone or together with taste exposure, on food acceptance by infants and young children ages 4 to 24 months because there are substantial concerns with consistency and directness in the body of evidence. (Grade: Grade Not Assignable)

##### Synthesis of the evidence: repeated taste and non-taste exposure and acceptance of a target food

The body of evidence examining the effects of repeated non-taste exposure either alone or together with taste exposure included 6 articles (5 independent studies), 4 RCTs^4,7,11,13,15^ and 1 NRCT.^21^

Three articles examined the effects of repeated non-taste exposure on the acceptance of a target food.^7,11,21^ In 1 study, 3 groups received a non-taste exposure intervention and 1 group that was exposed to an initially novel vegetable consumed significantly more of the target vegetable compared to the control (non-target) vegetable after the 2-week exposure period.^11^ There were no differences in vegetable intake for the groups exposed to an initially liked or initially disliked vegetable. There was no difference in willingness to taste a target vegetable versus a non-target vegetable for any group.^11^ The other 2 studies examined the effect of non-taste exposure to multiple novel fruits and vegetables on willingness to taste and had mixed findings.^7,21^ One study found that 4-week exposure to either set A target foods comprised of sweet potatoes, green pepper, rhubarb, and dried figs or set B target foods comprised of butternut squash, broad beans, dried prunes, and pomegranates resulted in tasting more of the target foods versus the non-target foods.^7^ However, there were differences in willingness to taste the target foods between groups such that the group exposed to set B increased their willingness to taste the target foods versus the group exposed to set A which had no differences in willingness to taste the target foods.^7^ One study investigated the effects of 2-week non-taste exposure to novel and familiar fruits and vegetables on willingness to taste at post intervention.^21^ Familiar non-target fruits and vegetables were tasted more than familiar target fruits and vegetables.^21^ Additionally, familiar non-target fruits and vegetables were tasted more than unfamiliar non-target fruits and vegetables.^21^ There were no differences in willingness to taste familiar versus unfamiliar target foods.^21^ In summary, the effect of repeated non-taste exposure to novel target food(s) on acceptance of the same or different fruit or vegetable is inconclusive.

Three articles examined the effects of repeated non-taste exposure together with taste exposure on acceptance of a target food.^4,13,15^ One study showed that children who received both taste and non-taste exposure had a higher intake of target vegetables after the intervention, but there were no differences in intake for children receiving taste exposure only.^4^ It is noteworthy that this study assessed habitual intake using a food frequency questionnaire, rather than weighed intake of the target vegetable.^4^ One study reported an increase in intake of target vegetable due to repeated taste and non-taste exposure at post intervention, but no difference in intake of target fruit at post-intervention.^15^ This study also examined the effects of repeated taste and non-taste exposure on total fruit and vegetable intake but found no differences suggesting that effects of repeated exposure were specific to targeted fruits and vegetables.^15^ Another study showed no change in either target fruit or vegetable intake at post intervention.^13^ Increased parental report of liking for target vegetable but not target fruit was noted in 1 article,^15^ and an increased parental report of liking and willingness to taste for both target vegetable and target fruit was noted in another article.^13^ In summary, the small number of studies examining the combination of taste and non-taste repeated exposure on food acceptance show mixed findings.

##### Assessment of the evidence: repeated taste and non-taste exposure and acceptance of a target food

The body of evidence examining repeated taste and non-taste exposure to target fruit or vegetable and acceptance of target fruit or vegetable by infants and young children ages birth to 24 months included 6 articles (5 independent studies); 4 RCTs and 1 NRCT. The evidence supporting this conclusion could not be assigned a grade. There was a lack of directness in that some studies provided both taste and non-taste exposure, limiting the ability to directly isolate the effects of non-taste exposure. Results were inconsistent and design-related differences across studies in the types of non-taste exposure were also taken into account in grading the evidence. Some concerns about precision and significant concerns about generalizability also influenced the grade assigned to this evidence. Although risk of publication bias is always of potential concern, small studies reporting both significant and null findings were included in this review. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The assessment of each grading element used when considering the strength of the evidence is outlined and described below.

###### Consistency

There were concerns with consistency. Findings are inconsistent in direction such that the effect of repeated non-taste exposure alone or together with taste exposure to target fruits and vegetables on acceptance of fruits and vegetables cannot be determined. The studies combined taste and non-taste exposures and the non-taste component was highly variable across the body of evidence.

###### Precision

There were some concerns with precision due to small sample sizes and because only 1 study reported a priori power analysis and was sufficiently powered.

###### Risk of bias

The risk of bias summary tables (Table 14, Table 15, Table 16) indicated certain areas that may be of concern for internal validity purposes. These included concern for bias in the measurement outcomes associated with perceived liking (due in part to lack of blinding of researchers, outcome assessors, or participants) and to some extent use of less valid tool to assess intake, limited reporting of randomization methods, missing data and lack of evidence for a pre-analysis plan, and not accounting for key confounders for non-randomized control trials. However, it was determined that these were not considered to be significant limitations for the body of evidence given that a good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.

###### Directness

There were some concerns with the directness of studies due to the way repeated non-taste exposure was tested in the body of evidence.

###### Generalizability

There were significant concerns regarding the lack of diversity in participant race/ethnicity and socio-economic position as well as the generalizability of international studies to the U.S. population. Most participants in the body of evidence were from relatively high socioeconomic backgrounds with little racial/ethnic diversity reported. Lack of information on SEP measures, and lack in standardization of reporting for studies that reported on SEP measures made information on education and income difficult to interpret. The majority of evidence included infants and young children within the U.S. and developed European countries aged 4 to 24 months; however, there are differences with respect to complementary feeding practices, cultural foods, diets, and eating values and norms between countries. This body of evidence is both practically and clinically important to the U.S. population because it addresses the critical issue of introduction of foods and the development of healthy eating habits.

Table 6 Conclusion statements and grades for repeated taste exposure to vegetable and food acceptance by infants and young children birth to 24 months of age

Conclusion Statement | Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. | Repeated taste exposure to a vegetable is likely to increase acceptance of a different vegetable, but not a fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate | Moderate
Body of Evidence | 13 articles: 10 RCTs and 2 NRCTs | 11 articles: 10 RCTs and 1 NRCT
Consistency | The body of evidence is consistent in direction of effects, with 12 of 13 studies demonstrating effects on 1 or more indicators of acceptance. | The body of evidence is consistent in the direction of effects, with 8 of 11 studies demonstrating effects on 1 or more indicators of acceptance.
Precision | The body of evidence has some concerns with precision due to small sample sizes and lack of power analysis. | The body of evidence has some concerns with precision due to small sample sizes and lack of power analysis.
Conclusion Statement | Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. | Repeated exposure to foods and food acceptance Repeated taste exposure to a vegetable is likely to increase acceptance of a different vegetable, but not a fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate.
Risk of bias | The body of evidence has some concerns with risk of bias due to limited reporting on randomization process, potential for missing data, selection of reported results, confounding, and measurement of outcomes associated with perceived liking. | The body of evidence has some concerns with risk of bias due to limited reporting on randomization process, potential for missing data, selection of reported results, confounding and measurement of outcomes associated with perceived liking.
Directness | The body of evidence consists of RCTs which are directly designed to address this question. | The body of evidence consists of RCTs which are directly designed to address this question.
Generalizability | The body of evidence has serious concerns with generalizability relative to the U.S. population because participants lacked diversity with respect to race/ethnicity and socioeconomic position. | The body of evidence has serious concerns with generalizability relative to the U.S. population because participants lacked diversity with respect to race/ethnicity and socioeconomic position.

Table 7 Conclusion statements and grades for repeated taste exposure to fruit and food acceptance by infants and young children ages birth to 24 months

Conclusion Statement | Repeated taste exposure to a single fruit is likely to increase acceptance of the target fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate. | Repeated taste exposure to a fruit may increase acceptance of a different fruit, but not a vegetable, by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as limited.
Grade | Moderate | Limited
Body of Evidence | 5 articles: 3 RCTs and 1 NRCT | 3 articles: 2 RCTs and 1 NRCT
Consistency | The body of evidence is consistent in direction of effects, with 4 of the 4 studies demonstrating effects on 1 more indicators of acceptance. | The body of evidence has some concerns with consistency in direction of effects.
Precision | The body of evidence has some concerns with precision due to small sample sizes and lack of power analysis. | The body of evidence has some concerns with precision due to small sample sizes and lack of power analysis.
Risk of bias | The body of evidence has some concerns with risk of bias due to limited reporting on randomization process, potential for missing data, selection of reported results, confounding and measurement of outcomes associated with perceived liking. | The body of evidence has some concerns with risk of bias due to limited reporting on randomization process, potential for missing data, selection of reported results, confounding and measurement of outcomes associated with perceived liking.
Directness | The body of evidence consists of RCTs which are directly designed to address this question. | The body of evidence consists of RCTs which are directly designed to address the question.
Generalizability | The body of evidence has serious concerns with generalizability relative to the U.S. population because the studies lacked diversity with respect to race/ethnicity and socioeconomic position. | The body of evidence has serious concerns with generalizability relative to the U.S. population because the studies lacked diversity with respect to race/ethnicity and socioeconomic position.

Table 8 Conclusion statement and grade for repeated non-taste exposure to fruits and/or vegetables and food acceptance by infants and young children ages birth to 24 months

Conclusion Statement | A conclusion statement cannot be drawn about the effect of repeated non-taste exposure, either alone or together with taste exposure, on food acceptance by infants and young children ages 4 to 24 months because there are substantial concerns with consistency and directness in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 6 articles: 4 RCTs and 1 NRCT
Rationale | There are substantial concerns with directness and consistency in the body of evidence. Studies that evaluated non-taste exposure in tandem with taste exposure were not designed to directly isolate the effect of non-taste exposure. Some concerns about precision (small number of studies, small sample sizes) and significant concerns about generalizability were also noted.

## Children (2 to 6 years)

### Description of the evidence

#### Design

The body of evidence on repeated exposure to a food(s) by children and food acceptance included 20 articles: 18 articles were from RCTs^22–39^ and 2 articles were from NRCTs.^40,41^ Analytic sample sizes ranged from 29 participants^41^ to 447 participants.^36^ Three studies had fewer than 50 participants,^22,40,41^ 5 studies had between 50 and 100 participants,^24,25,27,29,31^ and 12 studies had greater than 100 participants.^23,26,28,30,32–39^ (Table 17)

##### Setting

Most studies were conducted in settings outside the home: 4 studies took place at a day-care or child-care center,^22,36,39,41^ 8 studies took place at a preschool or nursery school,^23–25,27,29,34,35,37^ and 3 studies took place at a kindergarten.^31–33^ Five studies were conducted in the child’s home.^26,28,30,38,40^

##### Foods

###### Types of foods

The majority of articles tested the effects of repeated taste exposure to vegetables. Fourteen articles tested the effect of repeated taste exposure to a single vegetable or multiple vegetables^22,23,25,26,28–30,32,33,35–39^ and 1 study tested repeated taste exposure to a legume.^41^ Vegetables included as target foods in the repeated taste exposure interventions included: spinach, chicory, red bell pepper, yellow squash, sugar snap peas, broccoli, cauliflower, tomato, cucumber, carrot, radish, salsify, artichoke, mooli, pumpkin, zucchini, daikon, and/or green beans.

###### Familiarity

A majority of studies in children utilized familiar foods^22,23,25,26,28–30,36–38^; 7 of 10 studies using familiar foods tested the effects of repeated exposure to an initially disliked vegetable.^22,25,26,28,30,37,38^ Five studies tested repeated exposure to an unfamiliar target food (vegetable or legume).^23,29,35,36,41^ Foods were selected at group level in most studies. Three studies selected target foods at an individual level by having a parent select a least liked vegetable from a list.^26,30,38^

###### Amount, Timing, Preparation

Of the 15 studies examining repeated taste exposure, in 12 studies children were offered small “tastes” or “bites” of the vegetable and instructed to eat as much or as little as they wanted.^22,23,27,29,30,32,33,35,36,38,39^ The snack-sized portion ranged from 5 pieces to 100g.^23,32,33,36,39^ Two studies reported offering children a small taste.^22,30^ In Holley et al.^30^ parents offered their child a small piece (~2.5g) of a vegetable and in Anzman-Frasca et al.^22^ children were offered a small taste (~4g) of a target vegetable. Of the 2 studies that didn’t report the amount offered during the intervention, 1 study reported that parents offered their child a taste of a vegetable and 1 study reported that children were offered a puree 2-3 times per week before lunch.^29,38^

Taste exposures were typically offered alone at snack times or the start of lunch. A few studies chose times to offer the target foods that were between meals and snacks. In 1 study parents prepared a vegetable for their child and offered it at a predictable time (either before lunch or a snack).^26^ In 1 study lentils were offered in portions (24.4±0.4g) between breakfast and lunch or between lunch and afternoon snack.^41^ Holley et al.^30^ reported that parents provided vegetables outside of mealtimes and Anzman-Frasca et al.^22^ reported that repeated taste exposures occurred about 1 hour prior to lunch. In Vandeweghe et al.^37^ children participated in individual taste trials that took place before snack time. Children were offered a bowl (60g) of a vegetable (chicory) and asked to taste a small portion (4g).^37^

The form of the target food (pieces, puree, grated, etc.) differed between studies.^22,23,25,26,29,30,35–37,39^ Eight studies reported offering the target foods as bite-sized pieces (either raw or cooked)^23,29^ and 2 studies reported offering the target food in pureed form.^23,29^ Of the other studies, 1 study did not report on how the vegetable was offered,^38^ 1 study offered lentils that had been boiled and cooled,^41^ and 1 study offered different forms of the food to groups participating in the intervention.^32^ In this study, the target vegetable, daikon, was offered as sticks, triangles, or grated.^32^ One study also tested the effect of repeated taste exposure to daikon but only in the grated form.^33^ One study offered the target vegetable using different preparation methods.^28^ In de Wild et al.^28^ the target food, spinach, was offered either plain (chopped and served warm), creamed (chopped spinach with added cream), or as ravioli (70% spinach).

#### Repeated exposure interventions

##### Number, frequency, duration

The number of total exposures to each target food ranged from 5^36^ to 14^30^ with 10 exposures most commonly reported.^25,29,35,38,39^ The total duration of exposure periods ranged from 2 weeks^26,30,32^ to 21 weeks.^39^ The frequency of taste exposures varied from 1 time per week^28^ with the majority of studies testing 1 taste exposure per day.^25,26,30,36,38–40^ Only 1 study examined different exposure frequencies (2 times per week, 1 time per week, and 1 time per 2 weeks) and compared their effectiveness on increasing acceptance of the target vegetable.^33^

##### Type of repeated exposure

Of the 20 studies, 18 included a taste component to the intervention^22,23,25–33,35–39,41^ and 5 included a non-taste component.^24,27,31,34,40^ Of those 5 studies, 2 studies examined the effects of non-taste exposure combined with taste-exposure.^27,31^ In these studies children participated in exploratory activities focused on the target food followed by a tasting session.

Non-taste exposure included visual exposure to the target food(s) in the form story books read to the child^24,34,40^ and sensory play activities that provided sensory exposure involving sound, sight, touch and smell, such as listen to the vegetable name, tapping the vegetable to hear a sound, look at different versions of the vegetable and describe the color, feel the texture of the different forms, and pick and sniff the different forms.^34^ All studies assessed the effect of repeated non-taste exposure on willingness to taste, 2 of the studies assessed the effects on intake^24,34^ and 1 study assessed liking.^40^

#### Study Population

Six studies were conducted in the U.K.,^27,30,34,35,38,40^ 4 studies were conducted in the United States,^22,24,25,41^ 3 studies conducted in Netherlands^28,36,39^ 3 studies were conducted in Denmark,^29,32^ and 1 study was conducted in each of the following countries: Finland^31^, Australia^26^, France^23^, and Belgium.^37^

All of the RCTs took place in a preschool setting or with families with a preschool-aged child. Seventeen articles reported the mean child age, which a ranged from 2.11^39^ to 5.16 years.^26^ Most studies included children with an average age between 3 and 6 years.^22,24–26,30–35,37,38,41^ Studies with children older than 6 years were excluded unless the mean age of the participants was within the 2-to-6-year range.^38^ Child age and sex were well distributed within the body of evidence; all but 2 articles reported on children’s sex with samples ranging from 39% female^22^ to 58.2% female.^30^

Eight studies included information related to race and ethnicity for mothers and/or children.^22,24,25,27,30,38,40,41^ Of these, 7 studies included data from mostly (>69%) white participants.^25,27,30,38,40,41^ Of the other race/ethnicities represented in these studies, 3 studies included data from participants who identified as black ranging from 5-38% of the final,^24,25,30^ 6 studies included data from participants who identified as Asian/South Asian ranging from 1.7-15% of the final sample,^22,24,25,27,30,40^ and 2 studies included data from participants who identified as Hispanic ranging from 6-14% of the final sample.^25,40^

Other measures of socioeconomic position, specifically parental education, were reported in 10 of the articles.^22,25–27,30,31,38–41^ The methods for reporting parental education were highly variable between studies but in most studies, a majority of parents held a 4-year degree or higher (ranging from 53-93% of the final sample).^22,25,26,30,38–41^ One study reported that around 25% of parents held a University or polytechnic degree^31^ and 1 study reported that the mean years of education parents received was approximately 16 years.^27^ In studies that reported on additional levels of education, the percent of parents with a non-University degree or less ranged from around 7% to 47%.^26,30,39,40^ Household income, specifically, was reported in 1 study and indicated a majority of participants (77%) reported income of greater than $60,000.^22^

#### Outcomes

For this body of evidence, a change in acceptance was assessed by a change in at least 1 of the following 3 behavioral measures: food intake,^22,23,25,26,28–30,32–35,37–41^ food liking,^22–24,26–28,30,32,33,38,40,41^ and/or willingness to taste.^24,31,34–40^ Intake was assessed using weighed intake and in 1 study, using a food frequency questionnaire.^40^ Liking was typically assessed by child ratings using a 3-point hedonic scale although in some cases, perceived liking was assessed using parent, teacher and/or experimenter ratings.^23,27,40^ Willingness to taste included: parent-reported target food acceptance,^40^ willingness to consume bite of target food^24,31,35,36,39^ and likelihood of consuming target food.^34^ Table 9 indicates the food acceptance measures examined by included studies and exposure type.

Table 9 Food acceptance outcome indicators by study and exposure type by children (2 to 6 years)

Study | Number of studies/Exposure type | Intake | Liking | Willingness to taste
2 studies: O’Connell, 2012 ^25^ ; Hausner, 2012 ^29^ | 2 State | X
8 Studies: Karagiannaki, 2021 ^32^ ; Karagiannaki, 2021 ^33^ ; de Wild, 2016 ^28^ ; Ramsay 2017 ^41^ ; Corsini, 2013 ^26^ ; Holley, 2015 ^30^ ; Anzman-Frasca, 2012 ^22^ , Bouhlal, 2014 ^23^ | 8 Taste | X | X
3 Studies: Van Belkom, 2023 ^36^ ; Byrne 2002 ^24^ ; Hoppu, 2015 ^31^ | 1 Taste 1 Non-taste 1 Both taste and non-taste | | | X
3 Studies: Masento, 2022 ^40^ ; Vandeweghe, 201837; Wardle, 2003 ^38^ | 2 Taste 1 Non-taste | X | X | X
3 Studies: Nekitsing, 2019 ^35^ ; Nekitsing, 2019 ^34^ ; Zeinstra, 2018 ^39^ | 2 Taste 1 Non-taste | X | | X
1 Study: Coulthard, 2018 ^27^ | Both taste and non-Taste | | X
Total: 20 studies | | 16 | 12 | 9

### Conclusion statements and grades: taste exposure

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between repeated exposure to foods and food acceptance?” based on their review of the body of evidence examining repeated taste exposure and food acceptance by children ages 2 to 6 years.

#### Conclusion statement and grade

Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by children ages 2 to 6 years. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

##### Synthesis of the evidence: repeated taste exposure to a target vegetable and acceptance of a target vegetable

Fourteen studies evaluated effects of repeated taste exposure to 1 or more target vegetables on intake of the same vegetable,^22,23,25,26,28–30,32,33,35–39^ and 1 study tested repeated taste exposure to a legume.^41^ Vegetables included as target foods in the repeated taste exposure interventions included: spinach, chicory, red bell pepper, yellow squash, sugar snap peas, broccoli, cauliflower, tomato, cucumber, carrot, radish, salsify, artichoke, mooli, pumpkin, zucchini, daikon, and/or green beans. Of the 14 studies that examined repeated taste exposure to 1 or more vegetables, 12 reported an increase in weighed intake after the exposure.^22,23,26,28–30,32,33,35,37–39^ In the single study that examined repeated taste exposure to a legume, there was an overall increase in lentil intake from the pre-intervention period to the post-intervention period.^41^

Nine of 14 studies evaluated effects of repeated exposure to 1 or more target vegetables on liking of those foods.^22,23,26,28,30,32,33,37,38^ Of these, 6 studies found a positive effect on child-rated liking.^26,30,32,33,37,38^ In 1 study, children assigned to a repeated taste exposure intervention increased their rated liking of a target vegetable and had no changes in liking to a control vegetable (vegetable not included in the repeated exposure intervention).^22^ However, in a follow-up within-person study, a repeated taste exposure treatment was compared to an associative conditioning treatment in which the target vegetable was paired with a dip of the child’s choice.^22^ This study found a greater increase in liking for the target vegetable assigned to the associative conditioning treatment compared to the target vegetable assigned to the repeated exposure treatment.^22^ Another study assessed perceived liking using parent or teacher report and reported no difference in liking from pre-intervention to post-intervention for children repeatedly exposed to a basic salsify puree.^23^ De Wild et al.^28^ used paired preference tests to compare liking of the target vegetable (spinach) with a control vegetable (green beans) and found no shift in preference toward the target vegetable (spinach) from pre- to post-intervention. In Ramsay (2017),^41^ child-rated liking scores for lentils decreased from pre- to postintervention. In summary, a majority of controlled trials (6 of 9) demonstrated that providing repeated taste exposure to a vegetable resulted in increased liking of the target food; only 1 study^41^ investigated repeated taste exposure to a legume and found negative effects on perceived liking.

Five of 14 studies evaluated effects of repeated exposure to 1 or more target vegetables on willingness to taste.^35–39^ Two studies found no effect^35,37^ and 3 studies showed a positive effect.^36,38,39^ In summary, a small number of studies provided mixed evidence of effects of providing repeated taste exposure to vegetables on children’s willingness to taste.

##### Assessment of the evidence: repeated taste exposure to a target vegetable and acceptance of a target vegetable

The body of evidence examining repeated taste exposure to a target vegetable and acceptance of the target vegetable by children ages 2 to 6 years included 15 articles; 14 RCTs and 1 NRCT. Fifteen out of 15 studies demonstrating effects of repeated exposure to vegetables to increase 1 or more indicators of food acceptance. The available evidence was graded as moderate, primarily because studies were designed to directly answer the question, weighing heavily on RCT designs. Studies were also consistent in direction of effects. The reliance on RCT designs was considered to afford moderate protections against bias. These strengths were weighed against limitations concerning small sample sizes and the lack of evidence in U.S. population subgroups of diverse race and ethnicity as well as socioeconomic position. Although risk of publication bias is always of potential concern, small studies reporting both significant and null findings were included in this review. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The assessment of each grading element used when considering the strength of the evidence is outlined and described below.

###### Consistency

There were few to no concerns with consistency. Findings are consistent in direction such that there is a positive effect of repeated taste exposure from almost all studies on 1 or more indicators of acceptance. Weighed food intake was the predominant means of capturing an increase in acceptance and most studies showed increases in weighed intake following repeated exposure to the target vegetable. There was less consistency in the more subjective assessment of perceived liking. There were some important methodological differences across studies in terms of the foods provided as well as variations in number, frequency, and duration of repeated exposure.

###### Precision

There were few to no concerns related to precision. Seven studies reported a priori power analysis and 5 were sufficiently powered.

###### Risk of bias

The risk of bias summary tables (Table 18, Table 19, Table 20) indicated certain areas that may be of concern for internal validity purposes; These included limited reporting of randomization methods, missing data, and lack of evidence for a pre-analysis plan, and not accounting for key confounders for non-randomized control trials. However, It was determined that these were not considered to be significant limitations for the body of evidence given that a good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.

- Few studies reported the method for randomization of participants to the intervention and identified a pre-analysis plan. Limitations in these areas were considered to be more of a reporting issue than a flaw of the design. A good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.
- Missing data was not adequately described and accounted for numerous analyses.
- Study design: strongest design is within-subject design, with pre- and post-exposure measures, however this design was not used consistently across all studies. Some study designs lacked pre- and post-exposure measurements.

###### Directness

There were few to no concerns related to directness given that the preponderance of evidence involved RCT designs that were designed to directly examine the effect of repeated exposure on food acceptance by children ages 2 to 6 years. Some studies compared the effects of repeated taste exposure with other interventions (e.g., flavor-flavor learning, repeated exposure and rewards) on food acceptance, and some studies tested effects of repeated exposure to different forms of food on acceptance of that food; however, all involved at least 1 comparison where repeated exposure to a target food was compared to a control condition.

###### Generalizability

There were significant concerns regarding the lack of diversity in participant race/ethnicity and socio-economic position as well as the generalizability of international studies to the U.S. population; Most participants in the body of evidence were from relatively high socioeconomic backgrounds with little racial/ethnic diversity reported. Lack of information on SEP measures, and lack in standardization of reporting for studies that reported on SEP measures made information on education and income difficult to interpret. The majority of evidence included children within the U.S. and developed European countries aged 2 to 6 years; however, there are differences with respect to complementary feeding practices, cultural foods, diets, and eating values and norms between countries. This body of evidence is both practically and clinically important to the U.S. population because it addresses the critical issue of introduction of foods and the development of healthy eating habits.

#### Conclusion statement and grade

A conclusion statement cannot be drawn about the effect of repeated taste exposure to fruit(s) on acceptance of target fruit(s) by children ages 2 to 6 years because there is no evidence available. (Grade: Grade Not Assignable)

##### Synthesis of the evidence: repeated taste exposure to a target fruit and acceptance of a target fruit

Zero studies assessed the effect of repeated taste exposure of a target fruit on acceptance of the target fruit by children ages 2 to 6 years.

#### Conclusion statement and grade

Repeated taste exposure to a target vegetable may increase acceptance of a different vegetable by children ages 2 to 6 years. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

##### Synthesis of the evidence: repeated taste exposure to a target vegetable and acceptance of a different vegetable

Six studies examining repeated taste exposure to 1 or more target vegetables also tested the effects on acceptance of a different vegetable.^22,23,28,29,32,33^ Two of 6 studies showed an increase in intake.^28,29^ One of 6 studies showed increase in liking.^33^ Three of 6 studies showed no effect or mixed effects on liking.^22,23,32^ In 1 study, acceptance of multiple vegetables (cucumber, celery, broccoli, cauliflower, celeriac, and beetroot) was tested after children were repeatedly exposed to daikon.^32^ Cucumber and celery were used as dummy vegetables to test the 3-point smiley hedonic scale used by the children to determine liking. Cucumber was a generally liked vegetable (and the score almost always reached 3 on the hedonic scale), and celery was an unfamiliar vegetable. Changes in liking of different vegetables was mixed; for cauliflower, celery, and broccoli scores for liking decreased from pre-intervention to post-intervention (and follow-up) however, there were positive effects on liking for the vegetable celeriac and beetroot from pre- to post-intervention.^32^

##### Assessment of the evidence: repeated taste exposure to a target vegetable and acceptance of a different vegetable

The body of evidence examining repeated taste exposure to a target vegetable and acceptance of a different vegetable by children ages 2 to 6 years included 6 articles; 6 RCTs. A limited grade was assigned to the evidence supporting this conclusion statement. The use of RCT designs allowed direct evaluation of the association of interest but there were a small number of studies with inconsistent results. Concerns regarding consistency and lack of generalizability also influenced grading. Although risk of publication bias is always of potential concern, small studies reporting both significant and null findings were included in this review. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The assessment of each grading element used when considering the strength of the evidence is outlined and described below.

###### Consistency

There were some concerns with consistency. Findings are inconsistent across studies and within studies across different outcomes. There were methodological differences that were important to consider when synthesizing the evidence including variations in target and test foods across studies and variations in number, frequency, and duration of exposures.

###### Precision

There were some concerns with precision due to small sample sizes. Only 1 study reported a priori power analysis and was sufficiently powered.

###### Risk of bias

The evidence is from controlled trials using within-subject pre-/post-exposure measures of weighed food intake as the indicator of acceptance. The risk of bias summary tables (Table 18, Table 19, Table 20) indicated certain areas that may be of concern for internal validity purposes. These included concern for bias in limited reporting of randomization methods, missing data, and lack of evidence for a pre-analysis plan. However, it was determined that these were not considered to be significant limitations for the body of evidence given that a good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.

- Few studies reported the method for randomization of participants to the intervention and identified a pre-analysis plan. Limitations in these areas were considered to be more of a reporting issue than a flaw of the design. A good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.
- Missing data was not adequately described and accounted for numerous analyses.

###### Directness

There were few to no concerns related to directness given that the preponderance of evidence involved RCT designs that were designed to directly examine the effect of repeated exposure on food acceptability by children ages 2 to 6 years.

###### Generalizability

There were significant concerns regarding the lack of diversity in participant race/ethnicity and socio-economic position as well as the generalizability of international studies to the U.S. population. Most participants were from relatively high socioeconomic backgrounds, with little racial/ethnic diversity reported. Lack of information on SEP measures, and lack in standardization of reporting for studies that reported on SEP measures made information on education and income difficult to interpret. The majority of evidence included children within the U.S. and developed European countries aged 2 to 6 years; however, there are differences with respect to complementary feeding practices, cultural foods, diets, and eating values and norms between countries. This body of evidence is both practically and clinically important to the U.S. population because it addresses the critical issue of introduction of foods and the development of healthy eating habits.

#### Conclusion statement and grade

A conclusion statement cannot be drawn about the effect of repeated taste exposure to a target fruit on acceptance of a different fruit by children ages 2 to 6 years because there is no evidence (Grade: Grade Not Assignable)

##### Synthesis of the evidence: repeated taste exposure to a target fruit and acceptance of a different fruit

Zero studies assessed the effect of repeated taste exposure of a target fruit on acceptance of the different fruit by children ages 2 to 6 years.

### Conclusion statement and grade: non-taste exposure

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between repeated exposure to foods and food acceptance?” based on their review of the body of evidence examining repeated non-taste exposure and food acceptance by children ages 2 to 6 years.

#### Conclusion statement and grade

Repeated non-taste exposure alone or together with taste exposure to a target fruit or vegetable increases acceptance, specifically willingness to try, of the target fruit or vegetable by children ages 2 to 6 years. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

##### Synthesis of the evidence: repeated taste and non-taste exposure and acceptance of a target food

Five studies evaluated effects of repeated non-taste exposure on food acceptance either alone or combined with taste exposure and showed a positive effect on at least 1 indicator of food acceptance^24,27,31,34,40^: 4 out of 4 studies found positive effects on willingness to taste; 2 out of 2 studies showed positive effects on liking; and 1 out of 2 studies showed positive effects on intake.

Design and type of non-taste exposure employed varied considerably across studies. Three studies utilized story books, but the non-taste exposure varied across the studies.^24,34,40^ One of these studies tested the effects of repeated non-taste exposure to a target vegetable (Kohlrabi) on acceptance of the that food.^24^ In this study, children were read 1 of 2 modified books containing distinct and repeated messages about kohlrabi, a positive-message containing book (discovery of a liked taste to target vegetable) or negative-message containing book (a disliked taste to target vegetable).^24^ Willingness to taste was assessed from pre- to post-intervention. Results showed that willingness to taste was higher in both intervention groups regardless of whether the message was positive or negative.^24^ One limitation of the study was that the percentage of subjects tasting the kohlrabi at pretest was high (90%) in the positive message group, leaving little opportunity for increase.^24^ Another study tested the effects of repeated non taste exposure to an e-book portraying the ‘field to fork’ journey of a disliked target vegetable (vegetable chosen by parent from a list).^40^ After 14 repeated exposures to the story book, the intake (amount and frequency), liking, and willingness to taste was higher for the target vegetable compared to the control vegetable (not included in the non-taste exposure).^40^ Additionally, intake (amount and frequency), and willingness to taste increased from pre- to post-intervention for the target vegetable but not for the control vegetable, whereas liking increased for both the target and control vegetable from pre to post intervention, indicating some generalizability to different vegetable after repeated exposure to a target vegetable.^40^ The third study tested the effects of repeated non-taste exposure using 4 experimental groups: 2 storybook groups, 1 story featuring celeriac, an unfamiliar target vegetable, and another story featuring carrot, a familiar target vegetable, and 2 groups that combined a story book and sensory play, 1 group featuring celeriac and the other group featuring carrot.^34^ All 4 groups tested the acceptance of celeriac. Intake from pre- to post-intervention increased for all children except children in the carrot story book group.^34^ Children in the celeriac story book groups (both the story book group and story book plus sensory play group combined) had higher odds of willingness to taste celeriac compared to children in the carrot storybook groups at post-intervention, with children in in the celeriac story book and sensory play group having the highest odds of willingness to taste the celeriac at post-intervention.^34^ For children who were non-eaters at pre-intervention, the percentage of children who were willing to taste the celeriac at post-intervention was higher in the sensory play conditions compared with the story book only conditions.^34^

Two studies examined the effects of non-taste exposure in combination with taste exposure and showed a positive effect on food acceptance.^27,31^ Coulthard et al.^27^ compared repeated taste exposure alone, repeated taste and non-taste exposure combined, and a control group with no exposure, and showed that the group provided repeated taste and non-taste exposure to a target fruit (raspberry) had a higher liking for the same food compared to the control group (no taste and non-taste exposure). There were no differences in liking of raspberry between the group provided repeated taste exposure alone and the control group.^27^ Hoppu et al.^31^ assessed the change in willingness to taste the target fruits and vegetables from pre-intervention to post-intervention and showed that repeated taste and non-taste exposure combined increased willingness to taste some target vegetables including carrots and swede but not the other target vegetables and fruit including cabbage, rucola, romaine lettuce, and lingonberry.

Both studies also examined the effect of taste and non-taste exposure on acceptance of a different food.^27,31^ Coulthard et al.^27^ showed no differences between the group provided repeated taste and non-taste exposure to a target fruit (raspberry) and the control group (no taste and non-taste exposure) on liking of a different familiar or novel fruit (banana and lychee, respectively).^27^ Hoppu et al.^31^ showed that willingness to taste a new fruit (bilberries) increased from pre-intervention to post-intervention after repeated taste and non-taste exposure to multiple vegetables and fruit (carrots, cabbage, swede, rucola, romaine, and lingonberries).^31^

##### Assessment of the evidence: repeated taste and non-taste exposure and acceptance of a target food

The body of evidence examining repeated non-taste exposure either alone or together with taste exposure to target fruit and vegetable and acceptance of fruit and vegetable by children ages 2 to 6 years included 5 articles; 4 RCTs and 1 NRCT. A moderate grade was assigned to the evidence supporting this conclusion statement with 5 of 5 studies demonstrated effects of repeated non-taste exposure to a target vegetable on 1 or more indicator of acceptance. The reliance on RCT designs also was considered to afford moderate protections against bias. These strengths were weighed against the lack of evidence in U.S. population subgroups of diverse race and ethnicity as well as socioeconomic position. Although risk of publication bias is always of potential concern, small studies reporting both significant and null findings were included in this review. However, while the literature search was comprehensive, a search of the gray literature was not done, which could increase the possibility of publication bias. The assessment of each grading element used when considering the strength of the evidence is outlined and described below.

###### Consistency

There were few concerns related to consistency. Findings are consistent in direction such that there is a positive effect of repeated non-taste, or non-taste and taste, exposure on acceptance of the target food in children, but there were only a few studies assessed in the body of evidence.

###### Precision

There were few concerns with precision. The sample sizes were adequate and though only 2 studies reported a priori power analysis, 1 of them was sufficiently powered.

###### Risk of bias

The majority of the evidence is from controlled trials using within-subject pre-/post-exposure measures of weighed food intake as the indicator of acceptance. The risk of bias summary tables (Table 18, Table 19, Table 20) indicated certain areas that may be of concern for internal validity purposes. These included concern for bias in the measurement outcomes associated with perceived liking (due in part to lack of blinding of researchers, outcome assessors, or participants), limited reporting of randomization methods, missing data and lack of evidence for a pre-analysis plan, and not accounting for key confounders for non-randomized control trials. However, it was determined that these were not considered to be significant limitations for the body of evidence given that a good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.

- Measurement of perceived liking: Risk for bias is higher for more subjective assessments such as rating perceived liking compared to measures of weighed intake which is more objective.
- Few studies reported the method for randomization of participants to the intervention and identified a pre-analysis plan. Limitations in these areas were considered to be more of a reporting issue than a flaw of the design. A good number of studies considered were published prior to the registration of clinical trials and prior to the time when those aspects of study design were standard reporting requirements in peer reviewed journals.
- Missing data was not adequately described and accounted for numerous analyses.
- Study design: strongest design is within-subject design, with pre- and post-exposure measures, however this design was not used consistently across all studies. Some study designs lacked pre-/post-exposure measurements; between-subject measurements are not as strong.

###### Directness

There were few concerns related to directness. Most studies in this body of evidence are designed to directly examine the effect of repeated non-taste, or non-taste and taste, exposure on food acceptance by children ages 2 to 6 years. However, willingness to taste was the predominant means of capturing an increase in acceptance, which is a more subjective means of assessment compared with weighed food intake.

###### Generalizability

There were significant concerns regarding the lack of diversity in participant race/ethnicity and socio-economic position as well as the generalizability of international studies to the U.S. population. Lack of information on SEP measures, and lack in standardization of reporting for studies that reported on SEP measures made information on education and income difficult to interpret. The majority of evidence included children within the U.S. and developed European countries aged 2 to 6 years; however, there are differences with respect to complementary feeding practices, cultural foods, diets, and eating values and norms between countries. This body of evidence is both practically and clinically important to the U.S. population because it addresses the critical issue of introduction of foods and the development of healthy eating habits.

Table 10 Conclusion statements and grades for repeated taste exposure to vegetables and food acceptance by children ages 2 to 6 years

Conclusion Statement | Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by children ages 2 to 6 years. This conclusion statement is based on evidence graded as moderate. | Repeated taste exposure to a target vegetable may increase acceptance of a different vegetable by children ages 2 to 6 years. This conclusion statement is based on evidence graded as limited.
Grade | Moderate | Limited
Body of Evidence | 15 articles: 14 RCTs and 1 NRCT | 6 articles: 6 RCTs
Consistency | The body of evidence is consistent in direction of effects, with 14 of 15 studies demonstrating effects on 1 or more indicators of acceptance. | The body of evidence shows considerable variation in direction of effects.
Precision | The body of evidence has no concerns with precision because studies had adequate sample sizes and were sufficiently powered. | The body of evidence has some concerns with precision due to small sample sizes and lack of power analysis.
Risk of bias | The body of evidence has some concerns with risk of bias due to potential for confounding, missing data, and selection of reported results. | The body of evidence concerns due to potential for confounding, missing data, and selection of reported results.
[underlined: Directness] | The body of evidence is directly designed to address the question. | The body of evidence is directly designed to address the question.
[underlined: Generalizability] | The body of evidence has serious concerns with generalizability relative to the U.S. population, because participants lacked diversity with respect to race/ethnicity and socioeconomic position. | The body of evidence has serious concerns with generalizability relative to the U.S. population, because participants lacked diversity with respect to race/ethnicity and socioeconomic position.

Table 11 Conclusion statement and grades for repeated taste exposure to fruit and food acceptance by children ages 2 to 6 years

Conclusion Statement | A conclusion statement cannot be drawn about the effect of repeated taste exposure to fruit(s) on acceptance of target fruit(s) by children ages 2 to 6 years because there is no evidence available. | A conclusion statement cannot be drawn about the effect of repeated taste exposure to a target fruit on acceptance of a different fruit by children ages 2 to 6 years because there is no evidence available.
Grade | Grade Not Assignable | Grade Not Assignable
Body of Evidence/Rationale | No studies assessed the effect of repeated taste exposure of a target fruit on acceptance of the target fruit by children ages 2 to 6 years. | No studies assessed the effect of repeated taste exposure of a target fruit on acceptance of the different fruit by children ages 2 to 6 years.

Table 12 Conclusion statement and grades for repeated non-taste exposure to fruits and/or vegetables and food acceptance by children ages 2 to 6 years

Conclusion Statement | Repeated non-taste exposure alone or together with taste exposure to a target fruit or vegetable increases acceptance, specifically willingness to try, of the target fruit or vegetable by children ages 2 to 6 years. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 5 articles: 4 RCTs and 1 NRCT
Consistency | The body of evidence is consistent in direction of effects, with 5 of 5 studies demonstrating effects on 1 indicators of acceptance.
Precision | The body of evidence has no concerns with precision because studies had adequate sample sizes and were sufficiently powered.
Risk of bias | The body of evidence has some concerns with risk of bias due to potential for errors in measurement of outcome (perceived liking), missing data and selection of reported results.
Directness | The body of evidence was directly designed to address the question.
Generalizability | The body of evidence has serious concerns with generalizability relative to the U.S. population because participants lacked diversity with respect to race/ethnicity and socioeconomic position.