# Methods

The Committee used NESR’s methodology to conduct this systematic review. NESR’s methodology is described in detail in its methodology manual,^*^ as well as in the Committee’s Scientific Report.^†^ This section presents an overview of the specific methods used to answer the systematic review question: What is the relationship between repeated exposure to foods and food acceptance?

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

† Spill M, Callahan E, Johns K, . Repeated Exposure to Foods and Early Food Acceptance: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0401

This systematic review is an update to an existing NESR systematic review completed as part of the P/B-24 Project by the Flavor Exposure and Feeding Practices Technical Expert Collaborative on repeated exposure to foods and early food acceptance,^†^ which included evidence published from January 1980 to June 2017. This update synthesized all of the eligible studies conducted from January 1980 to May 2023 (infants and young children) and January 2000 and May 2023 (children) to develop and grade conclusion statements according to the methods described below. This means that all of the eligible articles from the existing review and the newly published articles were re-synthesized as 1 body of evidence.

## Develop a protocol

A systematic review protocol is the plan for how NESR’s methodology will be used to conduct a specific systematic review and is established by the Committee, a priori, before any evidence is reviewed. The protocol is designed to capture the most appropriate and relevant body of evidence to answer the systematic review question. Development of the protocol involves discussion of the strengths and limitations of various methodological approaches relevant to the question, which then inform subsequent steps of the systematic review process. The protocol describes all of the methods that will be used throughout the systematic review process. Additionally, the protocol includes the following components, which are tailored to each systematic review question: the analytic framework, the inclusion and exclusion criteria, and the synthesis plan. The Committee used the analytic framework and the inclusion and exclusion criteria from the existing review and made adjustments to the protocol, as needed. Differences in the inclusion and exclusion criteria between existing and updated reviews are documented in Appendix 3.

The protocol was posted online (https://nesr.usda.gov/protocols) for the public to view and comment on. Revisions to the systematic review protocol were made during the review process. These revisions are documented in Table 2.

Table 2 Protocol revisions

Date | Protocol change | Description
January 2024 | Inclusion and exclusion criteria for publication date were updated to document that the review will include studies published through May 2023. | This revision was made to document the final publication date range covered by the literature search.
July 2023 | Key definitions were added to the analytic framework for ‘target food’, ‘novel food’ and ‘familiar food’ | The additional key definitions were added to promote clarity.
July 2023 | The synthesis organization section of the analytic framework was revised to indicate that within population groups, the evidence will first be synthesized by intervention/exposure type – taste and non-taste repeated exposure to food, and then by outcome. | The revisions to the synthesis organization were made to provide transparency to the way in which the evidence was synthesized.

## Develop an analytic framework

An analytic framework visually represents the overall scope of the systematic review question and depicts the contributing elements that were examined and evaluated. It presents the core elements of each systematic review question, including the Population (i.e., those who experience the intervention/exposure and/or outcome), Intervention and/or exposure (i.e., the independent variable of interest), Comparator (i.e., the alternative being compared to the intervention or exposure), and Outcome(s). Definitions for key terms are also included because they provide the basis for how concepts are operationalized throughout the review. The expert group identified key confounders based on their knowledge of the nutrition and health research and experience as subject matter experts. Key confounders are participant characteristics such as health status, demographics, and diet and lifestyle behaviors, and/or other factors related to both the intervention/exposure and the outcome of interest that may impact the relationships of interest. Key confounders were considered during review and evaluation of the evidence, particularly during the risk of bias assessment of non-randomized and observational studies.

Figure 1 is the analytic framework for the systematic review. The intervention or exposure of interest was repeated exposure in infants and young children (birth to 24 months) and children (2 to 6 years); the comparators were pre-exposure versus post-exposure (within-subject) of a target food, no exposure versus exposure (between subjects) of a target food, and taste exposure versus non-taste exposure; the outcome was acceptance of food/s in infants and young children and children and adolescents; and the key confounders included race and/or ethnicity, socioeconomic position and/or parental education. The confounders may impact the relationship of interest.

Figure 1 Analytic framework for the systematic review question: What is the relationship between repeated exposure to foods and food acceptance?

Population | Intervention/exposure | Comparator | Outcome | Key confounders
Infants and young children (birth to 24 months) | Repeated exposure to food or food-type – child is exposed to a target food multiple times | - Pre-exposure versus post-exposure (within-subject); - No exposure versus exposure (between subjects); - Taste exposure versus non-taste exposure | Food acceptance of the exposed food (in infants, young children, children); - Amount or rate of target or novel food consumed; - Length of feeding of target or novel food during infant-led feeding; - Facial or body response (expressions made during feeding/eating of target or novel food); - Caregiver’s or investigator’s perception of infants’ enjoyment of the target or novel food; - Willingness to try or taste the target or novel food; - Hedonic responses; - Child’s verbal indication of liking of food | - Race and/or ethnicity; - Socioeconomic position (SEP) and/or parental education
Children (2 to 6 years) | Repeated exposure to food or food-type – child is exposed to a target food multiple times | - Pre-exposure versus post-exposure (within-subject); - No exposure versus exposure (between subjects); - Taste exposure versus non-taste exposure | | - Race and/or ethnicity; - Socioeconomic position (SEP) and/or parental education

Synthesis organization:

I. Population: Infants and young children; children
  a. Intervention/exposure: (Taste exposure, non-taste exposure)
    i. Outcome: food acceptance (amount and rate of food intake, length of feed, facial or body responses, enjoyment of food, willingness to try/taste food, hedonic responses, and child’s verbal indication of liking of food)

Key definitions:

[underlined: Exposure]: each time a child is exposed to target food(s) (taste and non-taste exposure).

[underlined: Repeated exposure:] child is exposed to a target food/food-type multiple times.

[underlined: Number of exposures]: times target food(s) is exposed.

[underlined: Duration of exposure period:] time from first exposure to last exposure.

[underlined: Frequency of exposures:] number of exposures per unit of time (per day, per week, etc.).

[underlined: Taste exposure:] taste exposure to the target food.

[underlined: Non-taste exposure]: Sensory exposure to the target food without tasting. Non-taste sensory exposure includes smell, tactile and visual exposure. Visual exposure could include looking at target food or a picture of a target food.

[underlined: Single food exposed]: Target food is a single food that is presented during each exposure period.

[underlined: Multiple foods exposed:] More than 1 target food is used during the exposure.

○ A single target food is presented within an exposure session; the target food may differ from session to session.
○ Multiple target foods are presented within each exposure session.

[underlined: Target food:] A target food is the food to which the child is provided repeated exposure to during the intervention.

[underlined: Novel food:] A novel food is a new food or a food that the child does not have experience with prior to the intervention.

[underlined: Familiar food:] A familiar food is a food the child has experience with prior to the intervention.

[underlined: Food acceptance, as measured by:]

- Amount or rate of target or novel food(s) consumed, as measured by research staff or reported by caregiver
- Duration of feeding of target or novel food(s) during infant-led feeding
- Facial response (expressions made during feeding of target or novel food(s))
- Caregiver perception of infants’ enjoyment of the target or novel food(s)
- Willingness to try or taste the target or novel food(s)
- Hedonic responses (child or caregiver reported liking using facial or descriptive scale)
- Child’s verbal indication of liking of food(s)

## Develop inclusion and exclusion criteria

The inclusion and exclusion criteria provide an objective, consistent, and transparent framework for determining which articles to include in the systematic review (Table 3). These criteria ensure that the most relevant and appropriate body of evidence is identified for the systematic review question, and that the evidence reviewed is^*^:

- Applicable to the U.S. population of interest
- Relevant to Federal public health nutrition policies and programs
- Rigorous from a scientific perspective

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials *; * Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials ^†^; † Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies
Publication date | - Infants and young children: January 1980 – May 2023 ^‡^; ‡ This review update date range encompasses the original systematic review date range, which included articles published from January 1980 to June 2017; - Additional search to cover children 2 to 6 y: January 2000 – May 2023 | - Infants and young children: Before January 1980, after May 2023; - Additional search to cover children 2 to 6 y: before January 2000, after May 2023
Population: Study participants | - Human | - Non-human
Population: Life stage | - At intervention or exposure:; - º Infants and young children (birth to 24 months); - º Children (2 to 6 years); - At outcome:; - º Infants and young children (birth to 24 months); - º Children and adolescents (2 to 19 years) | - At intervention or exposure:; - º School-aged children and adolescents (6 to 19 years); - º Adults and older adults (19 years and older); - At outcome:; - º Adults and older adults (19 years and older)
Population: Health status | - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease ^§^; § Studies that enroll participants who are at risk for chronic disease were included; - Studies that enroll [underlined: some] participants:; - º diagnosed with a disease;; - º diagnosed with a disease, disorder, or condition that affects feeding/eating or growth (e.g., autism spectrum disorder, attentiondeficit/hyperactivity disorder, eating disorder, cleft palate);; - º with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - º born preterm, ** with low birth weight, ^††^ and/or small for gestational age; ** Gestational age <37 weeks and 0/7 days; †† Birth weight <2500g; - º and/or hospitalized for an illness, injury or surgery | - Studies that [underlined: exclusively] enroll participants:; - º diagnosed with a disease; ^‡‡^; ‡‡ Studies that exclusively enroll participants with obesity were included; - º diagnosed with a disease, disorder, or condition that affects feeding/eating or growth (e.g., autism spectrum disorder, attentiondeficit/hyperactivity disorder, eating disorder, cleft palate);; - º with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - º born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age;; - º and/or hospitalized for an illness, injury, or surgery^§§^; §§ Studies that exclusively enroll participants post-cesarean section were included
Intervention/exposure | - Repeated exposure to target food(s): child is exposed to a target food/food-type multiple times; - Repeated exposure may address:; - º Number of exposures: times target food is exposed; - º Duration of exposure period; - º Frequency or number of exposure (per unit of time; per day, per week etc.); - º Type of repeated exposure:; - ▪ Taste and non-taste sensory exposure (smell, tactile, visual); - ▪ Single food: A single target food is presented during each exposure period; - ▪ Multiple foods: More than 1 target food is presented during exposure period; - A single target food is presented within an exposure session; the target food may differ from session to session; - Child is exposed to multiple target foods within each exposure session; - Multi-component intervention in which the isolated effect of the intervention of interest on the outcome(s) of interest is provided or can be determined despite multiple components | - Multi-component intervention in which the isolated effect of repeated food exposure on food acceptance is not provided or cannot be determined due to multiple components; - Food or flavor exposure in utero or via breastmilk; - Intervention assessing exposure to taste and/or flavor (e.g., salty, bitter, sweet) versus food
Comparator | - Pre-exposure versus post-exposure (within-subject); - No exposure versus exposure (between subjects); - Taste exposure versus non-taste sensory exposure (between subjects) | - N/A
Outcomes | - Acceptance of food as measured by; - º Amount or rate of target or novel food consumed as measured by research staff or reported by caregiver; - º Length of feeding of target or novel food during infant-led feeding paradigm; - º Facial response (expressions made during feeding of target or novel food) Caregiver or investigator’s perception of infants’ enjoyment of the target or novel food; - º Willingness to try/taste; - º Hedonic responses; - º Child’s verbal indication of liking of food | - Acceptance to taste and/or flavor (e.g., sweet, salty, etc.) versus food; - Nutrient intake (e.g., sodium)
Publication status | - Peer-reviewed articles published in research journals | - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings
Language | - Published in English | - Not published in English
Country^*^; * The classification of countries on the Human Development Index (HDI) is based on the UN Development Program Human Development Report Office (http://hdr.undp.org/en/data) for the year the study intervention occurred or data were collected. If the study does not report the year(s) in which the intervention/exposure data were collected, the HDI classification for the year of publication is applied. Studies conducted prior to 1990 are classified based on 1990 HDI classifications. If the year is more recent than the available HDI values, then the most recent HDI classifications are used. If a country is not listed in the HDI, then the current country classification from the World Bank is used (The World Bank Country and Lending Groups, available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected | - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected

## Search for and screen studies

NESR librarians, in collaboration with NESR analysts and the Committee, used the analytic framework and inclusion and exclusion criteria to develop a comprehensive literature search strategy. The literature search strategy included selecting and searching the appropriate bibliographic databases, translating search using syntax appropriate for the databases being searched, and employing search refinements, such as search filters. For existing reviews, search strategies will be updated, as appropriate, for each database. The full literature search is documented in Appendix 4.

The results of all electronic database searches, after removal of duplicates, were screened independently by 2 NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles meet the inclusion criteria. Manual searching was conducted to find peer-reviewed published articles not identified through the electronic database search. These articles were also screened independently by 2 NESR analysts at the abstract and full-text levels.

## Extract data and assess the risk of bias

NESR analysts extracted all essential data from each included article to describe key characteristics of the available evidence, such as the author, publication year, cohort/trial name, study design, population life stage at intervention/exposure and outcome, intervention/exposure and outcome assessment methods, and outcomes. One NESR analyst extracted the data and a second NESR analyst reviewed the extracted data for accuracy. Each article included in the systematic review underwent a formal risk of bias assessment, with 2 NESR analysts independently completing the risk of bias assessment using the tool that is appropriate for the study design.^†^,^‡^,^§^

† Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898 31462531

‡ Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919 27733354

§ Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602.

## Synthesize the evidence

The Committee described, compared, and combined the evidence from all included studies to answer the systematic review question.^**^ Synthesis of the body of evidence involved identifying overarching themes or key concepts from the findings, identifying and explaining similarities and differences between studies, and determining whether certain factors impact the relationships being examined, which includes potential causes of heterogeneity across all included evidence.

** USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Extracted data and risk of bias assessments for all included studies were tabulated to visually display results and facilitate synthesis. During the synthesis, the Committee considered the effect, direction, magnitude, and statistical significance of the results reported across the articles included in the body of evidence. The evidence was synthesized qualitatively without meta-analysis of effect estimates, statistical pooling or conversion of data, or quantitative tests of heterogeneity.

The synthesis plan for this review was designed with the end-use in mind, to inform the Committee’s advice to HHS and USDA regarding dietary guidance across life stages. The first level of synthesis organization was by population at intervention or exposure, which includes Infants and young children (birth to 24 months) and children (2 to 6 years). Then, within each of the population groups, the evidence was organized by similar intervention (taste exposure, non-taste exposure) based on the available evidence. The next level of organization was according to similar outcome.

## Develop conclusion statements and grade the evidence

After the Committee synthesized the body of evidence, they drafted conclusion statements. A conclusion statement is 1 or more summary statements carefully constructed to answer the systematic review question. Each conclusion statement reflects the evidence reviewed, as outlined in the analytic framework (e.g., PICO elements) and synthesis plan, and does not take evidence from other sources into consideration. Conclusion statements do not draw implications and should not be interpreted as dietary guidance. The Committee reviewed, discussed, and revised the conclusion statements until they reached agreement on wording that accurately reflected the body of evidence.

The Committee then developed conclusion statements by starting with the conclusion from the existing review and determining whether updates were needed based on the newly published evidence. In doing so, the Committee determined if the existing conclusion statements and grades should be retained without any modifications or should be updated to appropriately reflect both the existing review and the newer evidence.^**^

The Committee then graded the strength of the evidence underlying each conclusion statement. They did this using NESR’s predefined criteria, based on 5 grading elements: consistency, precision, risk of bias, directness and generalizability of the evidence. Study design and publication bias were also considered.^*^

- [underlined: Consistency]: Consistency considers the degree of similarity in the direction and magnitude of effect across the body of evidence. This element also considers whether differences across the results can be explained by variations in study designs and methods.
- [underlined: Precision]: Precision considers the degree of certainty around an effect estimate for a given outcome. This element considers measures of variability, such as the width and range of confidence intervals, the number of studies, and sample sizes, within and across studies.
- [underlined: Risk of bias]: Risk of bias considers the likelihood that systematic errors resulting from the design and conduct of the studies could have impacted the accuracy of the reported results across the body of evidence.
- [underlined: Directness]: Directness considers the extent to which studies are designed to directly examine the relationship among the interventions/exposures, comparators, and outcome(s) of primary interest in the systematic review question.
- [underlined: Generalizability:] Generalizability considers whether the study participants, interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population of interest for the review.

* Spill MK, English LK, Raghavan R, . Perspective: USDA Nutrition Evidence Systematic Review Methodology: Grading the Strength of Evidence in Nutrition- and Public Health-Related Systematic Reviews. Adv Nutr. 2022 Aug 1;13(4):982–991. doi: 10.1093/advances/nmab147 34918032

The Committee assigned a grade to each conclusion statement (i.e., strong, moderate, limited, or grade not assignable). The grade communicates the strength of the evidence supporting a specific conclusion statement to decision makers and stakeholders. A conclusion statement can receive a grade of Strong, Moderate, or Limited, and if insufficient or no evidence is available to answer a systematic review question, then no grade is assigned (i.e., Grade Not Assignable) (Table 4). The overall grade is not based on a predefined formula for scoring or tallying ratings of each element. Rather, each overall grade reflects the expert group’s thorough consideration of all of the grading elements, as they each relate to the specific nuances of the body of evidence under review.

Table 4 Definitions of NESR grades

Grade | Definition
Strong | The conclusion statement is based on a strong body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is strong, such that if new evidence emerges, modifications to the conclusion are unlikely to be required.
Moderate | The conclusion statement is based on a moderate body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is moderate, such that if new evidence emerges, modifications to the conclusion may be required.
Limited | The conclusion statement is based on a limited body of evidence as assessed by consistency, precision, risk of bias, directness, and generalizability. The level of certainty in the conclusion is limited, such that if new evidence emerges, modifications to the conclusion are likely to be required.
Grade Not Assignable | A conclusion statement cannot be drawn due to either a lack of evidence, or evidence that has severe limitations related to consistency, precision, risk of bias, directness, and generalizability.

The Committee assessed the newly synthesized evidence as it relates to the existing evidence. The Committee determined if the existing conclusion statements and grades should be retained without any modifications or should be updated to appropriately reflect both the existing review and the newer evidence.^*^

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual, Chapter 8: Updating NESR Systematic Reviews. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

## Recommend future research

The Committee identified and documented research gaps and methodological limitations throughout the systematic review process. These gaps and limitations will be used to develop research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on a particular topic. Rationales for the necessity of additional or stronger research are also be provided with the research recommendations.

## Peer review

This systematic review underwent external peer review in a process coordinated by staff from the National Institutes Health (NIH). NIH staff identified potential peer reviewers through outreach to a variety of professional organizations to select academic reviewers from U.S. colleges and universities across the country with a doctorate degree, including MDs, and expertise specific to the questions being reviewed. All peer reviewers were external to the Dietary Guidelines process, and therefore, current Committee members or Federal staff who supported the Committee or the development of the Dietary Guidelines were not eligible to serve as peer reviewers.

The peer review process was anonymous and confidential in that the peer reviewers were not identified to the Committee members or NESR staff, and in turn, the reviewers were asked not to share or discuss the review with anyone. Peer reviewers were made aware that per USDA, Food and Nutrition Service (FNS) agency policy, all peer reviewer comments would be summarized and made public, but comments would not be attributed to a specific reviewer.

Peer review occurred after draft conclusion statements were discussed by the full Committee at its third, fourth, fifth, and sixth public meetings. NIH staff assigned and distributed the reviews to at least 2 peer reviewers based on area of expertise. Following peer review, the Committee reviewed and discussed comments and made revisions to the systematic review, as needed, based on the discussion.

## Health equity considerations

The Committee was charged by HHS and USDA to review all scientific questions with a health equity lens to ensure that the next edition of the Dietary Guidelines is relevant to people with diverse racial, ethnic, socioeconomic, and cultural backgrounds. The Committee made a number of health equity considerations throughout the NESR systematic review process. The Committee’s Scientific Report^*^ includes a more detailed discussion of their approach to applying a health equity lens to their review of evidence, but examples include consideration of key confounders relevant to health equity and assessment of generalizability of the evidence.

* 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025