# Plain language summary

### What is the question?

The question is: What is the relationship between repeated exposure to foods and food acceptance? The population of interest for this question include infants and young children birth to 24 months and children 2 to 6 years.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated an existing review that was conducted as part of the Pregnancy and Birth to 24 Months Project (P/B-24 Project).

### What is the answer to the question?

#### Infants and young children (birth to 24 months)

- Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate.
- Repeated taste exposure to a single fruit is likely to increase acceptance of the target fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate.
- Repeated taste exposure to a vegetable is likely to increase acceptance of a different vegetable, but not a fruit by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as moderate.
- Repeated taste exposure to a fruit may increase acceptance of a different fruit, but not a vegetable, by infants and young children ages 4 to 24 months. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the effect of repeated non-taste exposure, either alone or together with taste exposure, on food acceptance by infants and young children ages 4 to 24 months because there are substantial concerns with consistency and directness in the body of evidence.

#### Children (2 to 6 years)

- Repeated taste exposure to a single or multiple novel or familiar vegetable(s) is likely to increase acceptance of the target vegetable(s) by children ages 2 to 6 years. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the effect of repeated taste exposure to fruit(s) on acceptance of target fruit(s) by children ages 2 to 6 years because there is no evidence available.
- Repeated taste exposure to a target vegetable may increase acceptance of a different vegetable by children ages 2 to 6 years. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the effect of repeated taste exposure to a target fruit on acceptance of a different fruit by children ages 2 to 6 years because there is no evidence available.
- Repeated non-taste exposure alone or together with taste exposure to a target fruit or vegetable increases acceptance, specifically willingness to try, of the target fruit or vegetable by children ages 2 to 6 years. This conclusion statement is based on evidence graded as moderate.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 1980 and May 2023 (infants and young children) and January 2000 and May 2023 (children).