# Appendix 5 Excluded articles

The existing systematic review^*^ for this question included 21 articles. However, after applying the inclusion and exclusion criteria established for the update to that review, only 14 remained eligible for inclusion. The following articles were excluded from the existing systematic review due to updated exposure eligibility criteria:

1. Brown MS, Grunfeld CC. Taste preferences of infants for sweetened or unsweetened foods. Res Nurs Health. 1980;3(1):11–17. doi:10.1002/nur.4770030104
2. Harris G, Booth DA. Infants’ preference for salt in food: Its dependence upon recent dietary experience. J. Reprod. Infant Psychol. 1987;5:97–104. doi:10.1080/02646838708403479
3. Hausner H, Nicklaus S, Issanchou S, Mølgaard C, Møller P. Breastfeeding facilitates acceptance of a novel dietary flavour compound. Clin Nutr. 2010;29(1):141–148. doi:10.1016/j.clnu.2009.11.007
4. Lundy B, Field T, Carraway K, et al. Food texture preferences in infants versus toddlers. Early Child Development and Care. 1998;146 (1):69–85. doi:10.1080/0300443981460107.
5. Maier AS, Chabanet C, Schaal B, Leathwood PD, Issanchou SN. Breastfeeding and experience with variety early in weaning increase infants’ acceptance of new foods for up to two months. Clin Nutr. 2008;27(6):849–857. doi:10.1016/j.clnu.2008.08.002
6. Stein LJ, Cowart BJ, Beauchamp GK. The development of salty taste acceptance is related to dietary experience in human infants: a prospective study. Am J Clin Nutr. 2012;95(1):123–129. doi:10.3945/ajcn.111.014282
7. Traoré T, Vieu MC, Alfred TS, Serge T. Effects of the duration of the habituation period on energy intakes from low and high energy density gruels by Burkinabè infants living in free conditions. Appetite. 2005;45(3):279–286. doi:10.1016/j.appet.2005.07.001

* Spill M, Callahan E, Johns K, Shapiro M, Spahn JM, Wong YP, Terry N, Benjamin-Neelon S, Birch L, Black M, Briefel R, Cook J, Faith M, Mennella J, Casavale KO, Stoody E. Repeated Exposure to Foods and Early Food Acceptance: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0401.

The following table lists the articles excluded after full-text screening for the updated systematic review question literature search (Appendix 3). At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 14 Articles excluded after full-text screening

| Citation | Reason(s) for exclusion
1 | Adepoju OT, Ayenitaju AO. Assessment of acceptability and nutrient content of palm weevil (Rhyncophorus phoenicis) larvae enriched complementary foods. International Journal of Tropical Insect Science. 2021;41:2263-2276. doi:10.1007/s42690-021-00487-7 | Intervention, country
2 | Ahern SM, Caton SJ, Blundell-Birtill P, Hetherington MM. The effects of repeated exposure and variety on vegetable intake in pre-school children. Appetite. 2019;132:37-43. doi:10.1016/j.appet.2018.10.001 | Study design
3 | Anggraini FD, Nisa F, Hasina SN, Munjidah A. The effect of nutritional education using cognitive approaches and psychomotor approaches on fruit and vegetable consumption behavior in children. Open Access Macedonian Journal of Medical Sciences. 2021;9:1161-1165 . doi:10.3889/oamjms.2021.7288 | Intervention
4 | Bobowski N, Mennella JA. Repeated exposure to low-sodium cereal affects acceptance but does not shift taste preferences or detection thresholds of children in a randomized clinical trial. Journal of Nutrition. 2019;149:870-876. doi:10.1093/jn/nxz014 | Intervention, age
5 | Bouhlal S, Issanchou S, Nicklaus S. The impact of salt, fat and sugar levels on toddler food intake. British Journal of Nutrition. 2011;105:645-653. doi:10.1017/S0007114510003752 | Intervention
6 | Braga-Pontes C, Simões-Dias S, Lages M, Guarino MP, Graça P. Nutrition education strategies to promote vegetable consumption in preschool children: the Veggies4myHeart project. Public Health Nutr. 2022;25(4):1061-1070. doi:10.1017/S1368980021004456 | Study design, intervention
7 | Canova A, Rollins BY, Francis LA. Cauliflower Power Storybooks and Cruciferous Vegetable Consumption in Preschool Children. J Nutr Educ Behav. 2021;53(4):359-362. doi:10.1016/j.jneb.2020.12.001 | Study design
8 | Chanadang S, Chambers IV E. Understanding children’s acceptability after repeated exposure and household-level behaviors for novel extruded fortified blended foods. Journal of Sensory Studies. 2020;35(4):e12530. doi:10.1111/joss.12530 | Country
9 | Chinchanachokchai S, Jamelske EM, Vernon E. Impact of teacher encouragement on children’s consumption and non-eating behaviour in a Wisconsin elementary school vegetable snack programme. Health Education Journal. 2022;81(3):265-79. doi:10.1177/00178969211073293 | Intervention
10 | Coulthard H, Sealy A. Play with your food! Sensory play is associated with tasting of fruits and vegetables in preschool children. Appetite. 2017;113:84-90. doi:10.1016/j.appet.2017.02.003 | Study design
11 | Coura CP, Monteiro LS, De Cnop ML, Minuzzo DA, Pereira RA. Innovative methods in nutritional interventions through sensory-based workshops with preschool children. Rev Nutr. 2022;35:e210227. https://doi.org/10.1590/1678-9865202235e2102 | Publication status
12 | da Costa SP, Remijn L, Weenen H, Vereijken C, van der Schans C. Exposure to texture of foods for 8-month-old infants: Does the size of the pieces matter?. J Texture Stud. 2017;48(6):534-540. doi:10.1111/jtxs.12271 | Outcome
13 | de Droog SM, Buijzen M, Valkenburg PM. Enhancing children’s Intervention vegetable consumption using vegetable-promoting picture books. The impact of interactive shared reading and character-product congruence. Appetite. 2014;73:73-80. doi:10.1016/j.appet.2013.10.018 | Intervention
14 | de Wild V, de Graaf C, Jager G. Effect of offering vegetables in different taste gradients on its acceptance in toddlers. Appetite. 2016;100(101):238. doi:10.1016/j.appet.2016.02.141 | Publication status
15 | DeJesus JM, Gelman SA, Herold I, Lumeng JC. Children eat more food when they prepare it themselves. Appetite. 2019;133:305-312. doi:10.1016/j.appet.2018.11.006 | Intervention
16 | Delisle Nyström C, Cameron AJ, Campbell KJ, Hesketh KD. Variation in outcomes of the Melbourne Infant, Feeding, Activity and Nutrition Trial (INFANT) according to maternal education and age 2 and 3·5 years post-intervention. Public Health Nutr. 2021;24(6):1460-1468. doi:10.1017/S1368980021000045 | Intervention
17 | Demonteil L, Tournier C, Marduel A, Dusoulier M, Weenen H, Nicklaus S. Longitudinal study on acceptance of food textures between 6 and 18 months. Food Quality and Preference. 2019;71:54-65. doi:10.1016/j.foodqual.2018.05.010 | Intervention
18 | Edwards KL, Thomas JM, Higgs S, Blissett J. Exposure to models’ positive facial expressions whilst eating a raw vegetable increases children’s acceptance and consumption of the modelled vegetable. Appetite. 2022;168:105779. doi:10.1016/j.appet.2021.105779 | Intervention
19 | Etuk REO, Forestell CA. Role of food neophobia and early exposure in children’s implicit attentional bias to fruits and vegetables. Appetite. 2021;167:105647. doi:10.1016/j.appet.2021.105647 | Intervention
20 | Farrow C, Belcher E, Coulthard H, et al. Using repeated visual exposure, rewards and modelling in a mobile application to increase vegetable acceptance in children. Appetite. 2019;141:104327. doi:10.1016/j.appet.2019.104327 | Intervention
21 | Maria M, Februhartanty J, Bardosono S. Association between food marketing exposure and consumption of confectioneries among pre-school children in Jakarta. Malaysian Journal of Nutrition. 2019:63-73. | Study design
22 | Fildes A, van Jaarsveld CHM, Wardle J, Cooke L. Parent-administered exposure to increase children’s vegetable acceptance: a randomized controlled trial. J Acad Nutr Diet. 2014;114(6):881-888. doi:10.1016/j.jand.2013.07.040 | Intervention
23 | Fuchs-Neuhold B, Staubmann W, Peterseil M, et al. Investigating New Sensory Methods Related to Taste Sensitivity, Preferences, and Diet of Mother-Infant Pairs and Their Relationship With Body Composition and Biomarkers: Protocol for an Explorative Study. JMIR Res Protoc. 2022;11(4):e37279. doi:10.2196/37279 | Intervention, publication status
24 | Garcia AL, Brown E, Goodale T, McLachlan M, Parrett A. A NurseryBased Cooking Skills Programme with Parents and Children Reduced Food Fussiness and Increased Willingness to Try Vegetables: A Quasi-Experimental Study. Nutrients. 2020;12(9):2623. doi:10.3390/nu12092623 | Intervention
25 | Gargiulo AH, De Queiroz Mello AP. Experience of implementing a food and nutrition education program for preschoolers. Mundo da Saude. 2021;45:162-174. doi:10.15343/0104-7809.202145162174 | Intervention
26 | Helland SH, Øverby NC, Myrvoll Blomkvist EA, et al. Wow! They really like celeriac! Kindergarten teachers’ experiences of an intervention to increase 1-year-olds’ acceptance of vegetables. Appetite. 2021;166:105581. doi:10.1016/j.appet.2021.105581 | Study design
27 | Helle C, Hillesund ER, Wills AK, Øverby NC. Evaluation of an eHealth intervention aiming to promote healthy food habits from infancy -the Norwegian randomized controlled trial Early Food for Future Health. Int J Behav Nutr Phys Act. 2019;16(1):1. doi:10.1186/s12966-018-0763-4 | Intervention
28 | Hohman EE, Paul IM, Birch LL, Savage JS. INSIGHT responsive parenting intervention is associated with healthier patterns of dietary exposures in infants. Obesity (Silver Spring). 2017;25(1):185-191. doi:10.1002/oby.21705 | Intervention
29 | Holley CE, Haycraft E, Farrow CV. Feeding practices and young children’s consumption of vegetables: The mediating role of food fussiness. Appetite. 2018;123:451.doi:10.1016/j.appet.2017.11.015 | Intervention
30 | Howard AJ, Mallan KM, Byrne R, Magarey A, Daniels LA. Toddlers’ food preferences. The impact of novel food exposure, maternal preferences and food neophobia. Appetite. 2012;59(3):818-825. doi:10.1016/j.appet.2012.08.022 | Study design, intervention
31 | Hughes L, Cirignano S, Fitzgerald N. Fruit and vegetable tastings in schools offer potential for increasing consumption among kindergarten through sixth grade children. Journal of the Academy of Nutrition and Dietetics. 2016;9(116):A19. doi:10.1016/j.jand.2016.06.054 | Publication status
32 | Jackson K, Jansen E, Mallan KM. Examining child intake frequency, mothers’ own liking and child early exposure as potential predictors of child liking for restricted foods and drinks at 5 years old. Public Health Nutr. 2020;23(13):2355-2364. doi:10.1017/S1368980020000312 | Intervention
33 | Johansson U, Öhlund I, Hernell O, Lönnerdal B, Lindberg L, Lind T. Protein-Reduced Complementary Foods Based on Nordic Ingredients Combined with Systematic Introduction of Taste Portions Increase Intake of Fruits and Vegetables in 9 Month Old Infants: A Randomised Controlled Trial. Nutrients. 2019;11(6):1255. doi:10.3390/nu11061255 | Intervention
34 | Johnson SL, Moding KJ, Grimm KJ, Flesher AE, Bakke AJ, Hayes JE. Infant and Toddler Responses to Bitter-Tasting Novel Vegetables: Findings from the Good Tastes Study. J Nutr. 2021;151(10):3240-3252. doi:10.1093/jn/nxab198 | Intervention
35 | Johnson SL, Moding KJ, Maloney K, Bellows LL. Development of the Trying New Foods Scale: A preschooler self-assessment of willingness to try new foods. Appetite. 2018;128:21-31. doi:10.1016/j.appet.2018.05.146 | Intervention
36 | Johnson SL, Ryan SM, Kroehl M, Moding KJ, Boles RE, Bellows LL. A longitudinal intervention to improve young children’s liking and consumption of new foods: findings from the Colorado LEAP study. Int J Behav Nutr Phys Act. 2019;16(1):49. doi:10.1186/s12966-019-0808-3 | Intervention
37 | Johnson SL, Shapiro ALB, Moding KJ, Flesher A, Davis K, Fisher JO. Infant and Toddler Consumption of Sweetened and Unsweetened Lipid Nutrient Supplements After 2-Week Home Repeated Exposures. J Nutr. 2021;151(9):2825-2834. doi:10.1093/jn/nxab148 | Intervention
38 | Kadey M. When at First You Don’t Succeed, Try Again … and Again. IDEA Fitness Journal. 2018;15:39-39 . | Study design
39 | Kalhoff H, Schmidt IV, Heindl I, Kunert J, Kersting M. Feeding frozen complementary foods promotes food acceptance in infants: The randomized intervention trial Baby Gourmet. Nutr Res. 2021;87:49-56. doi:10.1016/j.nutres.2020.12.020 | Intervention
40 | Kay MC, Hammad NM, Truong T, Herring SJ, Bennett GG. Feasibility, Acceptability, and Initial Efficacy of a Digital Intervention to Improve Consumption of Foods Received within a National Nutrition Assistance Program. Nutrients. 2023;15(2):438. doi:10.3390/nu15020438 | Intervention
41 | Komninou S, Halford JC, Harrold JA. The impact of maternal eating behaviour, infant temperament, and mother-infant interactions on vegetable feeding outcomes. Appetite. 2018;123:452. doi:10.1016/j.appet.2017.11.018 | Intervention
42 | Kristiansen AL, Bjelland M, Himberg-Sundet A, Lien N, Holst R, Frost Andersen L. Effects of a cluster randomized controlled kindergartenbased intervention trial on vegetable consumption among Norwegian 3-5-year-olds: the BRA-study. BMC Public Health. 2019;19(1):1098. doi:10.1186/s12889-019-7436-3 | Intervention
43 | Kristiansen AL, Medin AC, Bjelland M, et al. Long-term effects of a cluster randomized controlled kindergarten-based intervention trial on vegetable intake among Norwegian 3-5-year-olds: the BRA-study. BMC Res Notes. 2020;13(1):30. doi:10.1186/s13104-020-4892-x | Intervention
44 | Lanigan J, Bailey R, Jackson AMT, Shea V. Child-Centered Nutrition Phrases Plus Repeated Exposure Increase Preschoolers’ Consumption of Healthful Foods, but Not Liking or Willingness to Try. J Nutr Educ Behav. 2019;51(5):519-527. doi:10.1016/j.jneb.2019.02.011 | Intervention
45 | Lipsky LM, Burger K, Cummings JR, Faith MS, Nansel TR. Associations of parent feeding behaviors and early life food exposures with early childhood appetitive traits in an observational cohort study. Physiol Behav. 2023;265:114175. doi:10.1016/j.physbeh.2023.114175 | Outcome
46 | López M, Alcoceba I, Castro MJ, et al. Assessment of an Educational Intervention to Improve Healthy Life Habits in Children Living in Vulnerable Socioeconomic Conditions. Int J Environ Res Public Health. 2021;18(9):4495. doi:10.3390 /ijerph18094495 | Intervention
47 | Loth KA, Hersch D, Trofholz A, Harnack L, Norderud K. Impacts of COVID-19 on the home food environment and eating related behaviors of families with young children based on food security status. Appetite. 2023;180:106345. doi:10.1016/j.appet.2022.106345 | Intervention
48 | Masis N, Johnson SL, McCaffrey J, Chapman-Novakofski K. Fruit and Vegetable Preferences and Identification by Kindergarteners through 2nd-Graders With or Without the U.S. Department of Agriculture Fresh Fruit and Vegetable Program. J Nutr Educ Behav. 2017;49(9):752-758.e1. doi:10.1016/j.jneb.2017.05.349 | Study design
49 | Maxwell AE, Castillo L, Arce AA, De Anda T, Martins D, McCarthy WJ. Eating Veggies Is Fun! An Implementation Pilot Study in Partnership With a YMCA in South Los Angeles. Prev Chronic Dis. 2018;15:E132. doi:10.5888/pcd15.180150 | Age
50 | McGowan L, Cooke LJ, Gardner B, Beeken RJ, Croker H, Wardle J. Healthy feeding habits: efficacy results from a cluster-randomized, controlled exploratory trial of a novel, habit-based intervention with parents. Am J Clin Nutr. 2013;98(3):769-777. doi:10.3945/ajcn.112.052159 | Intervention
51 | McLeod CJ, Haycraft E, Daley AJ. Offering vegetables to children at breakfast time in nursery and kindergarten settings: the Veggie Brek feasibility and acceptability cluster randomised controlled trial. Int J Behav Nutr Phys Act. 2023;20(1):38. doi:10.1186/s12966-023-01443-z | Intervention
52 | Melnick EM, Thomas K, Farewell C, et al. Impact of a nutrition education programme on preschool children’s willingness to consume fruits and vegetables. Public Health Nutr. 2020;23(10):1846-1853. doi:10.1017/S1368980019005032 | Intervention
53 | Mennella JA, Daniels LM, Reiter AR. Learning to like vegetables during breastfeeding: a randomized clinical trial of lactating mothers and infants. Am J Clin Nutr. 2017;106(1):67-76. doi:10.3945/ajcn.116.143982 | Intervention
54 | Mobley AR, Gans KM, Adamsons K, Huedo-Medina TB. Feasibility, Acceptability, and Preliminary Outcomes of a Father-Focused Childhood Obesity Prevention Program for Low-Income Families with Preschool-Age Children. Child Obes. 2023;19(1):13-24. doi:10.1089/chi.2021.0225 | Intervention
55 | Moding KJ, Bellows LL, Grimm KJ, Johnson SL. A longitudinal examination of the role of sensory exploratory behaviors in young children’s acceptance of new foods. Physiol Behav. 2020;218:112821. doi:10.1016/j.physbeh.2020.112821 | Intervention
56 | Mohd Nor ND, Houston-Price C, Harvey K, Methven L. The effects of taste sensitivity and repeated taste exposure on children’s intake and liking of turnip (Brassica rapa subsp. rapa); a bitter Brassica vegetable. Appetite. 2021;157:104991. doi:10.1016/j.appet.2020.104991 | Intervention
57 | Momin SR, Hughes SO, Elias C, et al. Observations of Toddlers’ sensory-based exploratory behaviors with a novel food. Appetite. 2018;131:108-116. doi:10.1016/j.appet.2018.08.035 | Intervention
58 | Müller C, Chabanet C, Zeinstra GG, Jager G, Schwartz C, Nicklaus S. The sweet tooth of infancy: Is sweetness exposure related to sweetness liking in infants up to 12 months of age?. Br J Nutr. Published online August 11, 2022. doi:10.1017/S0007114522002628 | Intervention
59 | Perraud E, Parker HW, Tovar A, Kaar J, Vadiveloo M. The relationship between maternal prenatal and postnatal vegetable intake and repeated measures of infant vegetable intake frequency in a national U.S. sample. Appetite. 2022;168:105781. doi:10.1016/j.appet.2021.105781 | Intervention
60 | Poelman AAM, Cochet-Broch M, Cox DN, Vogrig D. VERTICAL: A Sensory Education Program for Australian Primary Schools to Promote Children’s Vegetable Consumption. J Nutr Educ Behav. 2017;49(6):527-528.e1. doi:10.1016/j.jneb.2017.04.001 | Outcome
61 | Poelman AAM, Delahunty CM, Broch M, de Graaf C. Multiple vs Single Target Vegetable Exposure to Increase Young Children’s Vegetable Intake. J Nutr Educ Behav. 2019;51(8):985-992. doi:10.1016/j.jneb.2019.06.009 | Intervention
62 | Reidy KC, Bailey RL, Deming DM, et al. Food Consumption Patterns and Micronutrient Density of Complementary Foods Consumed by Infants Fed Commercially Prepared Baby Foods. Nutr Today. 2018;53(2):68-78. doi:10.1097/NT.0000000000000265 | Intervention
63 | Roberts AP, Cross L, Hale A, Houston-Price C. VeggieSense: A non-taste multisensory exposure technique for increasing vegetable acceptance in young children. Appetite. 2022;168:105784. doi:10.1016/j.appet.2021.105784 | Intervention
64 | Roe LS, Meengs JS, Birch LL, Rolls BJ. Serving a variety of vegetables and fruit as a snack increased intake in preschool children. Am J Clin Nutr. 2013;98(3):693-699. doi:10.3945/ajcn.113.062901 | Study design
65 | Rollins BY, Stein W, Keller KL, Savage JS. Preschoolers will drink their GREENS! Children accept, like, and drink novel smoothies containing dark green vegetables (DGVs). Appetite. 2021;162:105148. doi:10.1016/j.appet.2021.105148 | Intervention
66 | Russell CG, Denney-Wilson E, Laws RA, et al. Impact of the Growing Healthy mHealth Program on Maternal Feeding Practices, Infant Food Preferences, and Satiety Responsiveness: Quasi-Experimental Study. JMIR Mhealth Uhealth. 2018;6(4):e77. doi:10.2196/mhealth.9303 | Intervention
67 | Schwartz C, Chabanet C, Szleper E, Feyen V, Issanchou S, Nicklaus S. Infant Acceptance of Primary Tastes and Fat Emulsion: Developmental Changes and Links with Maternal and Infant Characteristics. Chem Senses. 2017;42(7):593-603. doi:10.1093/chemse/bjx040 | Intervention
68 | Schwartz C, Madrelle J, Brignot H, et al. Acceptance of added fat to first complementary feeding purees: An exploration of fat type, feeding history and saliva composition. Appetite. 2018;131:160-168. doi:10.1016/j.appet.2018.08.007 | Intervention
69 | Tournier C, Bernad C, Madrelle J, et al. Fostering infant food texture acceptance: A pilot intervention promoting food texture introduction between 8 and 15 months. Appetite. 2021;158:104989. doi:10.1016/j.appet.2020.104989 | Intervention
70 | Tucker JM, DeFrang R, Orth J, Wakefield S, Howard K. Evaluation of a Primary Care Weight Management Program in Children Aged 2⁻5 years: Changes in Feeding Practices, Health Behaviors, and Body Mass Index. Nutrients. 2019;11(3):498. doi:10.3390/nu11030498 | Intervention
71 | van der Veek SMC, de Graaf C, de Vries JHM, et al. Baby’s first bites: a randomized controlled trial to assess the effects of vegetable-exposure and sensitive feeding on vegetable acceptance, eating behavior and weight gain in infants and toddlers. BMC Pediatr. 2019;19(1):266. doi:10.1186/s12887-019-1627-z | Study design
72 | van Vliet MS, Mesman J, Schultink JM, et al. Baby’s first bites: Association between observed maternal feeding behavior and infant vegetable intake and liking. Appetite. 2021;165:105316. doi:10.1016/j.appet.2021.105316 | Intervention
73 | van Vliet MS, Schultink JM, Jager G, et al. The Baby’s First Bites RCT: Evaluating a Vegetable-Exposure and a Sensitive-Feeding Intervention in Terms of Child Health Outcomes and Maternal Feeding Behavior During Toddlerhood. J Nutr. 2022;152(2):386-398. doi:10.1093/jn/nxab387 | Intervention
74 | Vennerød FF, Almli VL, Berget I, Lien N. Do parents form their children’s sweet preference? The role of parents and taste sensitivity on preferences for sweetness in pre-schoolers. Food Quality and Preference. 2017; 62:172-82. doi:10.1016/j.foodqual.2017.06.013 | Intervention
75 | Villafaña VN, Borrero CS. Evaluating the efficacy of pictorial preference assessments with children who engage in food selectivity. Behavioral Interventions. 2023;38(1):2-5. doi:10.1002/bin.1912 | Intervention
76 | Wagner S, Issanchou S, Chabanet C, Lange C, Schaal B, Monnery-Patris S. Weanling Infants Prefer the Odors of Green Vegetables, Cheese, and Fish When Their Mothers Consumed These Foods During Pregnancy and/or Lactation. Chem Senses. 2019;44(4):257-265. doi:10.1093/chemse/bjz011 | Intervention
77 | Wetherill MS, Williams MB, Reese J, et al. Methods for Assessing Willingness to Try and Vegetable Consumption among Children in Indigenous Early Childcare Settings: The FRESH Study. Nutrients. 2021;14(1):58. Published 2021 Dec 24. doi:10.3390/nu14010058 | Intervention
78 | Whiteside-Mansell L, Swindle TM. Evaluation of Together We Inspire Smart Eating: pre-school fruit and vegetable consumption. Health Educ Res. 2019;34(1):62-71. doi:10.1093/her/cyy048 | Intervention
79 | Wiggins S. How infant food likes become established as knowledge: Parental food assessments during infant mealtimes in the home. Appetite. 2023;184:106489. doi:10.1016/j.appet.2023.106489 | Intervention
80 | Yuan WL, Nicklaus S, Forhan A, et al. Associations between Infant Dietary Intakes and Liking for Sweetness and Fattiness Sensations in 8-to-12-Year-Old Children. Nutrients. 2021;13(8):2659. doi:10.3390/nu13082659 | Intervention, outcome