# Appendix 4 Literature search strategy

## Searches from existing review(s)

The literature search conducted for the existing review identified articles published between January 1980- June 2017.

For the complete search documentation, refer to:

Spill M, Callahan E, Johns K, Shapiro M, Spahn JM, Wong YP, Terry N, Benjamin-Neelon S, Birch L, Black M, Briefel R, Cook J, Faith M, Mennella J, Casavale KO, Stoody E. Repeated Exposure to Foods and Early Food Acceptance: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0401.

## Search A

The search was conducted to identify articles on taste-based exposures and food acceptance published between June 2017 and May 2023. The search was first run on April 15, 2022 and then periodically run using NESR’s continuous evidence monitoring methods^*^ until May 31, 2023.

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

### Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: April 15, 2022 (initial search); April 16 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: July 1, 2019 – May 31, 2023

Table A 4 Search for PubMed (Search A)

Search # | Concept | String
#1 | Foods | “Diet”[MeSH] OR “Meals”[MeSH] OR “Food and Beverages”[Mesh] OR “Edible Grain”[Mesh] OR meal*[tiab] OR food*[tiab] OR beverage*[tiab] OR eating[tiab] OR diet[tiab] OR diets[tiab] OR cereal*[tiab] OR bread*[tiab] OR whole grain*[tiab] OR juice*[tiab] OR milk[tiab] OR dairy[tiab] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR vegetable*[tiab] OR egg[tiab] OR eggs[tiab] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab] OR candy[tiab] OR “Fast Food*”[tiab] OR seeds[tiab] OR seafood[tiab] OR shellfish[tiab] OR fish[tiab] OR soymilk[tiab] OR wheat[tiab] OR “soy”[tiab] OR “soybean”[tiab]
#2 | Exposure | experience*[tiab] OR Exposures*[tiab] OR feed*[tiab] OR fed[tiab]
#3 | Acceptance | Food Preferences[MeSH] OR acceptability[tiab] OR acceptance[tiab] OR consum*[tiab] OR eats[tiab] OR eating[tiab] OR eaten[tiab] OR preference[tiab] OR liking[tiab] OR willingness[tiab] OR reject*[tiab] OR (increas*[tiab] AND intake[tiab])
#4 | 0-6 years old | “Infant”[MeSH] OR “Child, Preschool”[MeSH] OR infant[tiab] OR newborn[tiab] OR new-born[tiab] OR neonat*[tiab] OR baby[ti] OR babies[tiab] OR toddler[tiab] OR preschool*[tiab] OR “pre-school*”[tiab] OR “early childhood”[tiab] OR “young child*”[tiab] OR kindergarten[tiab] OR prekindergarten[tiab] OR “pre-kindergarten”[tiab] OR “pre-k”[tiab] OR “pre-primary”[tiab] OR “under 5”[tiab] OR “under five”[tiab] OR “first five years”[tiab] OR “first 5 years”[tiab]
#5 | | #1 AND #2 AND #3 AND #4
#6 | Limits | #5 NOT (”Animals”[Mesh] NOT (”Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR“retracted publication”[ti] OR ”Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Language: English; Publication Date: 2017/7/1 - 3000/12/12

### Database: Embase

Provider: Elsevier

Date(s) Searched: April 15, 2022 (initial search); April 16 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: July 1, 2019 – May 31, 2023

Table A 5 Search for Embase (Search A)

Search # | Concept | String
#1 | Foods | ‘diet’/exp OR ‘meal’/exp OR ‘Food’/exp OR ‘Beverages’/exp OR ‘meal*’:ab,ti OR ‘food*’:ab,ti OR ‘beverage*’:ab,ti OR ‘eating’:ab,ti OR ‘diet’:ab,ti OR ‘diets’:ab,ti OR ‘cereal*’:ab,ti OR ‘bread*’:ab,ti OR ‘whole grain*’:ab,ti OR ‘juice*’:ab,ti OR ‘milk’:ab,ti OR ‘dairy’:ab,ti OR ‘meat’:ab,ti OR ‘cheese’:ab,ti OR ‘yogurt’:ab,ti OR ‘yoghurt*’:ab,ti OR ‘fruit*’:ab,ti OR ‘vegetable*’:ab,ti OR ‘egg’:ab,ti OR ‘eggs’:ab,ti OR ‘nut’:ab,ti OR ‘nuts’:ab,ti OR ‘peas’:ab,ti OR ‘beans’:ab,ti OR ‘legume*’:ab,ti OR ‘snack*’:ab,ti OR ‘candy’:ab,ti OR ‘Fast Food*’:ab,ti OR ‘seeds’:ab,ti OR ‘seafood’:ab,ti OR ‘shellfish’:ab,ti OR ‘fish’:ab,ti OR ‘soymilk’:ab,ti OR ‘wheat’:ab,ti OR ‘soy’:ab,ti OR ‘soybean’:ab,ti
#2 | Exposure | ‘experience*’:ab,ti OR ‘exposures*’:ab,ti OR ‘feed*’:ab,ti OR ‘fed’:ab,ti
#3 | Acceptance | ‘Food Preference’/exp OR ‘acceptability’:ab,ti OR ‘acceptance’:ab,ti OR ‘consum*’:ab,ti OR ‘eats’:ab,ti OR ‘eating’:ab,ti OR ‘eaten’:ab,ti OR ‘preference’:ab,ti OR ‘liking’:ab,ti OR ‘willingness’:ab,ti OR ‘reject*’:ab,ti OR (‘increas*’ AND ‘intake’):ab,ti
#4 | 0-6 years old | ‘infant’/exp OR ‘preschool child’/exp OR ‘toddler’/exp OR infant:ab,ti OR newborn:ab,ti OR ‘new-born’:ab,ti OR neonat*:ab,ti OR baby:ab,ti OR babies:ab,ti OR toddler:ab,ti OR preschool*:ab,ti OR ‘pre-school*’:ab,ti OR ‘early childhood’:ab,ti OR ‘young child*’:ab,ti OR ‘kindergarten’:ab,ti OR ‘prekindergarten’:ab,ti OR ‘pre-kindergarten’:ab,ti OR ‘pre-k’:ab,ti OR ‘pre-primary’:ab,ti OR ‘under 5’:ab,ti OR ‘under five’:ab,ti OR ‘first five years’:ab,ti OR ‘first 5 years’:ab,ti
#5 | | #1 AND #2 AND #3 AND #4
#6 | Limits | #5 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti); AND [2017-2023]/py

### Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: April 15, 2022 (initial search); April 16 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: July 1, 2019 – May 31, 2023

Table A 6 Search for Cochrane CENTRAL (Search A)

Search # | Concept | String
#1 | Foods | [mh “diet”] OR [mh “meals”] OR [mh “Food and Beverages”] OR (“meal*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”):ti,ab,kw
#2 | Exposure | (“experience*” OR “exposures*” OR “feed*” OR “fed”):ti,ab,kw
#3 | Acceptance | [mh “Food Preferences”] OR (“acceptability” OR “acceptance” OR “consum*” OR “eats” OR “eating” OR “eaten” OR “preference” OR “liking” OR “willingness” OR “reject*” OR (“increas*” AND “intake”)):ti,ab,kw
#4 | 0-6 years old | [mh “Infant”] OR [mh “Child, Preschool”] OR (infant OR newborn OR “new-born” OR neonat* OR baby OR babies OR toddler OR preschool* OR “pre-school*”OR “early childhood” OR “young child*” OR kindergarten OR prekindergarten OR “pre-kindergarten” OR “prek” OR “pre-primary” OR “under 5” OR “under five” OR “first five years” OR “first 5 years”):ti,ab,kw
#5 | | #1 AND #2 AND #3 AND #4; In Trials, word variations searched; Publication Year: 2017-2023

### Database: CINAHL

Provider: EBSCO

Date(s) Searched: April 15, 2022 (initial search); April 16 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: July 1, 2019 – May 31, 2023

Table A 7 Search for CINAHL (Search A)

Search # | Concept | String
#1 | Foods | (MH “Diet+”) OR (MH “Meals+”) OR (MH “Food and Beverages+”) OR TI (“meal*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”) OR AB (“meal*” OR “feeding*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”)
#2 | Exposure | TI (“experience*” OR “exposures*” OR “feed*” OR “fed”) OR AB (“experience*” OR “exposures*” OR “feed*” OR “fed”)
#3 | Acceptance | [mh “Food Preferences”] OR TI (“acceptability” OR “acceptance” OR “consum*” OR “eats” OR “eating” OR “eaten” OR “preference” OR “liking” OR “willingness” OR “reject*” OR (“increas*” AND “intake”)) OR AB (“acceptability” OR “acceptance” OR “consum*” OR “eats” OR “eating” OR “eaten” OR “preference” OR “liking” OR “willingness” OR “reject*” OR (“increas*” AND “intake”))
#4 | 0-6 years old | (MH “Infant+”) OR (MH “Child, Preschool”) OR TI (infant OR newborn OR “new-born” OR neonat* OR baby OR babies OR toddler OR preschool* OR “pre-school*” OR “early childhood” OR “young child*”OR kindergarten OR prekindergarten OR “pre-kindergarten” OR “pre-k” OR “pre-primary” OR “under 5” OR “under five” OR “first five years” OR “first 5 years”) OR AB (infant OR newborn OR “new-born” OR neonat* OR baby OR babies OR toddler OR preschool* OR “pre-school*” OR “early childhood” OR “young child*” OR kindergarten OR prekindergarten OR “pre-kindergarten” OR “pre-k” OR “pre-primary” OR “under 5” OR “under five” OR “first five years” OR “first 5 years”)
#5 | | #1 AND #2 AND #3 AND #4
#6 | Limiters | #5 NOT ((MH “Animals+”) OR (MH “Animal Studies”)) NOT ((MH “Congresses and Conferences”) OR (MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Practice Guidelines”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication”)); Limiters - English Language, Expanders - Apply equivalent subject; Published Date: 20170701-20230531

### Database: Scopus

Provider: Clarivate

Date(s) Searched: April 15, 2022 (initial search); April 16 – May 31, 2023 (continuous evidence monitoring)

Dates Covered: July 1, 2019 – May 31, 2023

Table A 8 Search for Scopus (Search A)

Search # | Concept | String
#1 | Foods | TITLE-ABS-KEY(“meal*” OR “feeding*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”)
#2 | Exposure | TITLE-ABS-KEY(“experience*” OR “exposures*” OR “feed*” OR “fed”)
#3 | Acceptance | TITLE-ABS-KEY(“acceptability” OR “acceptance” OR “consum*” OR “eats” OR “eating” OR “eaten” OR “preference” OR “liking” OR “willingness” OR “reject*” OR (“increas*” AND “intake”)
#4 | 0-5 years old | TITLE-ABS-KEY(infant OR newborn OR “new-born” OR neonat* OR baby OR babies OR toddler OR preschool* OR “pre-school*”OR “early childhood” OR “young child*” OR kindergarten OR prekindergarten OR “pre-kindergarten” OR “pre-k” OR “pre-primary” OR “under 5” OR “under five” OR “first five years” OR “first 5 years”)
#5 | | #1 AND #2 AND #3 AND #4
#6 | Limiters | #5 AND NOT DOCTYPE ( bk OR ch OR cp OR cr OR ed OR er OR le OR pr OR re ) AND NOT SRCTYPE ( b OR k OR p OR n OR w OR l OR d ) AND ( LIMIT-TO ( PUBYEAR , 2023 ) OR LIMIT- TO ( PUBYEAR , 2022 ) OR LIMIT-TO ( PUBYEAR , 2021 ) OR LIMIT-TO ( PUBYEAR , 2020 ) OR LIMIT-TO ( PUBYEAR , 2019 ) OR LIMIT-TO ( PUBYEAR , 2018 ) OR LIMIT-TO ( PUBYEAR , 2017 ))

## Search B

The search was conducted to identify articles on non-taste-based exposures and food acceptance, published between January 2000 and May 2023. This search was done because these terms were not included in the existing review search or Search A.

### Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: May 31, 2023

Dates Covered: January 1, 2000 – May 31, 2023

Table A 9 Search for PubMed (Search B)

Search # | Concept | String
#1 | Selected Foods | “Diet”[MeSH] OR “Meals”[MeSH] OR “Food and Beverages”[Mesh] OR “Edible Grain”[Mesh] OR meal*[tiab] OR feeding*[tiab] OR food*[tiab] OR beverage*[tiab] OR eating[tiab] OR diet[tiab] OR diets[tiab] OR cereal*[tiab] OR bread*[tiab] OR whole grain*[tiab] OR juice*[tiab] OR milk[tiab] OR dairy[tiab] OR meat[tiab] OR cheese*[tiab] OR yogurt*[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR vegetable*[tiab] OR egg[tiab] OR eggs[tiab] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab] OR candy[tiab] OR “Fast Food*”[tiab] OR seeds[tiab] OR seafood[tiab] OR shellfish[tiab] OR fish[tiab] OR soymilk[tiab] OR wheat[tiab] OR “soy”[tiab] OR “soybean*”[tiab]
#2 | Exposure | experience*[tiab] OR Exposures*[tiab] OR feed*[tiab] OR fed[tiab] OR offer*[tiab] OR familiarizing[tiab] OR sensory[tiab] OR “picture book*”[tiab] OR storybook*[tiab]
#3 | Acceptance | Food Preferences[MeSH] OR acceptability[tiab] OR acceptance[tiab] OR consum*[tiab] OR eats[tiab] OR eating[tiab] OR eaten[tiab] OR preference[tiab] OR liking[tiab] OR willingness[tiab] OR reject*[tiab] OR (increas*[tiab] AND intake[tiab])
#4 | 0-6 years old | “Infant”[MeSH] OR “Child, Preschool”[MeSH] OR infant[tiab] OR newborn[tiab] OR new-born[tiab] OR neonat*[tiab] OR baby[ti] OR babies[tiab] OR toddler[tiab] OR preschool*[tiab] OR “pre-school*”[tiab] OR “early childhood”[tiab] OR “young child*”[tiab] OR kindergarten[tiab] OR prekindergarten[tiab] OR “pre-kindergarten”[tiab] OR “pre-k”[tiab] OR “pre-primary”[tiab] OR “under 5”[tiab] OR “under five”[tiab] OR “first five years”[tiab] OR “first 5 years”[tiab]
#5 | | #1 AND #2 AND #3 AND #4
#6 | Search B NOT Search A
#7 | | #6 NOT (”Animals”[Mesh] NOT (”Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR“retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Language: English; Publication Date: 2000/01/01- 3000/12/12

### Database: Embase

Provider: Elsevier

Date(s) Searched: May 31, 2023

Dates Covered: January 1, 2000 – May 31, 2023

Table A 10 Search for Embase (Search B)

Search # | Concept | String
#1 | Selected Foods | ‘diet’/exp OR ‘meal’/exp OR ‘Food’/exp OR ‘Beverages’/exp OR ‘meal*’:ab,ti OR ‘food*’:ab,ti OR ‘beverage*’:ab,ti OR ‘eating’:ab,ti OR ‘diet’:ab,ti OR ‘diets’:ab,ti OR ‘cereal*’:ab,ti OR ‘bread*’:ab,ti OR ‘whole grain*’:ab,ti OR ‘juice*’:ab,ti OR ‘milk’:ab,ti OR ‘dairy’:ab,ti OR ‘meat’:ab,ti OR ‘cheese’:ab,ti OR ‘yogurt’:ab,ti OR ‘yoghurt’:ab,ti OR ‘fruit*’:ab,ti OR ‘vegetable*’:ab,ti OR ‘egg’:ab,ti OR ‘eggs’:ab,ti OR ‘nut’:ab,ti OR ‘nuts’:ab,ti OR ‘peas’:ab,ti OR ‘beans’:ab,ti OR ‘legume*’:ab,ti OR ‘snack*’:ab,ti OR ‘candy’:ab,ti OR ‘Fast Food*’:ab,ti OR ‘seeds’:ab,ti OR ‘seafood’:ab,ti OR ‘shellfish’:ab,ti OR ‘fish’:ab,ti OR ‘soymilk’:ab,ti OR ‘wheat’:ab,ti OR ‘soy’:ab,ti OR ‘soybean’:ab,ti
#2 | Exposure | ‘experience*’:ab,ti OR ‘exposures*’:ab,ti OR ‘feed*’:ab,ti OR ‘fed’:ab,ti OR ‘offer*’:ab,ti OR ‘familiarizing’:ab,ti OR ‘sensory’:ab,ti OR ‘picture book*’:ab,ti OR ‘storybook*’:ab,ti
#3 | Acceptance | ‘Food Preference’/exp OR ‘acceptability’:ab,ti OR ‘acceptance’:ab,ti OR ‘consum*’:ab,ti OR ‘eats’:ab,ti OR ‘eating’:ab,ti OR ‘eaten’:ab,ti OR ‘preference’:ab,ti OR ‘liking’:ab,ti OR ‘willingness’:ab,ti OR ‘reject*’:ab,ti OR (‘increas*’ AND ‘intake’):ab,ti
#4 | 0-6 years old | ‘infant’/exp OR ‘preschool child’/exp OR ‘toddler’/exp OR infant:ab,ti OR newborn:ab,ti OR ‘new-born’:ab,ti OR neonat*:ab,ti OR baby:ab,ti OR babies:ab,ti OR toddler:ab,ti OR preschool*:ab,ti OR ‘pre-school*’:ab,ti OR ‘early childhood’:ab,ti OR ‘young child*’:ab,ti OR ‘kindergarten’:ab,ti OR ‘prekindergarten’:ab,ti OR ‘pre-kindergarten’:ab,ti OR ‘pre-k’:ab,ti OR ‘pre-primary’:ab,ti OR ‘under 5’:ab,ti OR ‘under five’:ab,ti OR ‘first five years’:ab,ti OR ‘first 5 years’:ab,ti
#5 | | #1 AND #2 AND #3 AND #4
#6 | Search B NOT Search A
#7 | | #6 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti)

### Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: May 31, 2023

Dates Covered: January 1, 2000 – May 31, 2023

Table A 11 Search for Cochrane (CENTRAL) (Search B)

Search # | Concept | String
#1 | Selected Food | [mh “diet”] OR [mh “meals”] OR [mh “Food and Beverages”] OR (“meal*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”):ti,ab,kw
#2 | Exposure | (“experience*” OR “exposures*” OR “feed*” OR “fed” OR offer* OR familiarizing OR sensory OR “picture book” OR “picture books” OR storybook*):ti,ab,kw
#3 | Acceptance | [mh “Food Preferences”] OR (“acceptability” OR “acceptance” OR “consum*” OR “eats” OR “eating” OR “eaten” OR “preference” OR “liking” OR “willingness” OR “reject*” OR (“increas*” AND “intake”)):ti,ab,kw
#4 | 0-6 years old | [mh “Infant”] OR [mh “Child, Preschool”] OR (infant OR newborn OR “new-born” OR “new-borns” OR neonat* OR baby OR babies OR toddler OR preschool* OR “pre-school” OR “preschools” OR “pre-schooler” OR “pre-schoolers” OR “early childhood” OR “young child” OR “young children” OR kindergarten OR prekindergarten OR “pre-kindergarten” OR “pre-k” OR “pre-primary” OR “under 5” OR “under five” OR “first five years” OR “first 5 years”):ti,ab,kw
#5 | | #1 AND #2 AND #3 AND #4
#6 | Search B NOT Search A | In Trials (Word variations have been searched)

### Database: CINAHL

Provider: EBSCO

Date(s) Searched: May 31, 2023

Dates Covered: January 1, 2000 – May 31, 2023

Table A 12 Search for CINAHL (Search B)

Search # | Concept | String
#1 | Selected Foods | (MH “Diet+”) OR (MH “Meals+”) OR (MH “Food and Beverages+”) OR TI (“meal*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”) OR AB (“meal*” OR “feeding*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”)
#2 | Exposure | TI (“experience*” OR “exposures*” OR “feed*” OR “fed” OR “offer*” OR familiarizing OR sensory OR “picture book*” OR storybook*) OR AB (“experience*” OR “exposures*” OR “feed*” OR “fed” OR “offer*” OR familiarizing OR sensory OR “picture book*” OR storybook*)
#3 | Acceptance | [mh “Food Preferences”] OR TI (“acceptability” OR “acceptance” OR “consum*” OR “eats” OR “eating” OR “eaten” OR “preference” OR “liking” OR “willingness” OR “reject*” OR (“ ncrease*” AND “intake”)) OR AB (“acceptability” OR “acceptance” OR “consum*” OR “eats” OR “eating” OR “eaten” OR “preference” OR “liking” OR “willingness” OR “reject*” OR (“ increase*” AND “intake”))
#4 | 0-5 years old | (MH “Infant+”) OR (MH “Child, Preschool”) OR TI (infant OR newborn OR “new-born” OR neonat* OR baby OR babies OR toddler OR preschool* OR “pre-school*” OR “early childhood” OR “young child*”OR kindergarten OR prekindergarten OR “pre-kindergarten” OR “pre-k” OR “pre-primary” OR “under 5” OR “under five” OR “first five years” OR “first 5 years”) OR AB (infant OR newborn OR “new-born” OR neonat* OR baby OR babies OR toddler OR preschool* OR “preschool*” OR “early childhood” OR “young child*” OR kindergarten OR prekindergarten OR “pre-kindergarten” OR “pre-k” OR “pre-primary” OR “under 5” OR “under five” OR “first five years” OR “first 5 years”)
#5 | | S1 AND S2 AND S3 AND S4
#6 | Updated search NOT existing search
#7 | | #6 NOT ((MH “Animals+”) OR (MH “Animal Studies”)) NOT ((MH “Congresses and Conferences”) OR (MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Practice Guidelines”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication”)) Limiters – English Language, Expanders – Apply equivalent subject Publication Year: 2000-2023

### Database: Scopus

Provider: Clarivate

Date(s) Searched: May 31, 2023

Dates Covered: January 1, 2000 – May 31, 2023

Table A 13 Search for Scopus (Search B)

Search # | Concept | String
#1 | Selected Foods | TITLE-ABS-KEY(“meal*” OR “feeding*” OR “food*” OR “beverage*” OR “eating” OR “diet” OR “diets” OR “cereal*” OR “bread*” OR “whole grain*” OR “juice*” OR “milk” OR “dairy” OR “meat” OR “cheese” OR “yogurt” OR “yoghurt*” OR “fruit*” OR “vegetable*” OR “egg” OR “eggs” OR “nut” OR “nuts” OR “peas” OR “beans” OR “legume*” OR “snack*” OR “candy” OR “Fast Food*” OR “seeds” OR “seafood” OR “shellfish” OR “fish” OR “soymilk” OR “wheat” OR “soy” OR “soybean”)
#2 | Exposure | TITLE-ABS-KEY(“experience*” OR “exposures*” OR “feed*” OR “fed” OR “offer*” OR familiarizing OR sensory OR “picture book*” OR storybook*)
#3 | Acceptance | TITLE-ABS-KEY(“acceptability” OR “acceptance” OR “consum*” OR “eats” OR “eating” OR “eaten” OR “preference” OR “liking” OR “willingness” OR “reject*” OR (“increas*” AND “intake”))
#4 | 0-6 years old | TITLE-ABS-KEY(infant OR newborn OR “new-born” OR neonat* OR baby OR babies OR toddler OR preschool* OR “pre-school*”OR “early childhood” OR “young child*” OR kindergarten OR prekindergarten OR “pre-kindergarten” OR “pre-k” OR “pre-primary” OR “under 5” OR “under five” OR “first five years” OR “first 5 years”)
#5 | | #1 AND #2 AND #3 AND #4
#6 | Search B NOT Search A
#7 | | #6 AND NOT DOCTYPE ( bk OR ch OR cp OR cr OR ed OR er OR le OR pr OR re ) AND NOT SRCTYPE ( b OR k OR p OR n OR w OR l OR d ) AND ( LIMIT-TO ( PUBYEAR , 2023 ) OR LIMIT-TO ( PUBYEAR , 2022 ) OR LIMIT-TO ( PUBYEAR , 2021 ) OR LIMIT-TO ( PUBYEAR , 2020 ) OR LIMIT-TO ( PUBYEAR , 2019 ) OR LIMIT-TO ( PUBYEAR , 2018 ) OR LIMIT-TO ( PUBYEAR , 2017 ) OR LIMIT-TO ( PUBYEAR , 2016 ) OR LIMIT-TO ( PUBYEAR , 2015 ) OR LIMIT-TO ( PUBYEAR , 2014 ) OR LIMIT-TO ( PUBYEAR , 2013 ) OR LIMIT-TO ( PUBYEAR , 2012 ) OR LIMIT-TO ( PUBYEAR , 2011 ) OR LIMIT-TO ( PUBYEAR , 2010 ) OR LIMIT-TO ( PUBYEAR , 2009 ) OR LIMIT-TO ( PUBYEAR , 2008 ) OR LIMIT-TO ( PUBYEAR , 2007 ) OR LIMIT-TO ( PUBYEAR , 2006 ) OR LIMIT-TO ( PUBYEAR , 2005 ) OR LIMIT-TO ( PUBYEAR , 2004 ) OR LIMIT-TO ( PUBYEAR , 2003 ) OR LIMIT-TO ( PUBYEAR , 2002 ) OR LIMIT-TO ( PUBYEAR , 2001 ) OR LIMIT-TO ( PUBYEAR , 2000 ) )