# Appendix 3 Inclusion and exclusion criteria comparison between existing and updated systematic reviews

Table A 3 Inclusion and exclusion criteria comparison between existing^*^ * Spill M, Callahan E, Johns K, . Repeated Exposure to Foods and Early Food Acceptance: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0401. and updated systematic reviews for the research question: What is the relationship between repeated exposure to foods and food acceptance?

Category | Existing Review | Updated Review | Change and Rationale
Study design | [underlined: Included]:; - Randomized controlled trials^†^; † Randomized Controlled trials include: factorial designs, cross-over designs; - Non-randomized controlled trials^‡^; ‡ Non-randomized controlled trials Include quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; [underlined: Excluded]:; - Cross-sectional studies; - Before and after study^§^; § Before and after study involves collecting data before and after an exposure with 2 different populations (i.e., 2 cross-sectional data sets are compared); - Uncontrolled studies; - Case-control studies; - Editorial, book chapters; - Narrative reviews; - Ecological studies (cross cultural studies; matching trends from different countries); - Systematic reviews; - Meta-analyses | [underlined: Included:]; - Randomized controlled trials; - Non-randomized controlled trials^**^; ** Including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; [underlined: Excluded:]; - Cross-sectional studies; - Uncontrolled trials^††^; †† Including uncontrolled before-and-after studies; - Case-control studies; - Narrative reviews; - Ecological studies; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies | Updated review includes nested casecontrol studies
Publication date | [underlined: Included]:; - January 1980 - June 2017; [underlined: Excluded]:; - Before January 1980 and after June 2017 | [underlined: Included]:; - Infants and young children: January 1980 – May 2023; - Additional search to cover children: January 2000 – May 2023; [underlined: Excluded]:; - Infants and young children: Before January 1980, and after TBD; - Additional search to cover children: before January 2000, after May 2023 | Updated review includes studies published after June 2017 to present for infants and young children.; New review includes studies published after Jan 2000 to May 2023 for children.
Population: Study participants | [underlined: Included]:; - Human subjects; - Males; - Females; - Pregnant women; - Lactating women; - Non-lactating postpartum women; [underlined: Excluded]:; - Hospitalized patients, not including birth and immediate post-partum hospitalization of healthy mothers and babies; - 100% pre-mature study population | [underlined: Included]:; - Human; [underlined: Excluded]:; - Non-human | No change
Population: Life stage | [underlined: Included]:; - Infants (0-12 months); - Young children (12-24 months)^*^; * Included studies with 0-24mo olds; included studies with age range exceeding 24mo if subgroup analysis was conducted on group ≤ 24 month; [underlined: Excluded]:; - Child (2-5 years); - Child (6-12 years); - Adolescents (13-18 years); - Adults (19 and older); - Older adults (65 to 79 years); - Older adults (80+ years) | [underlined: Included]:; - At intervention; - º Infants and young children (birth to 24 months); - º Children (2 to 6 years); - At outcome; - º Infants and young children (birth to 24 months); - º Children and adolescents (2 to 19 years); [underlined: Excluded]:; - At intervention/exposure and outcome; - º Adolescents (12 to 19 years) (for intervention/exposure only); - º Adults (19 years and older); - º Older adults (65 years and older) | Eligible population for this review was expanded to include children (2 to 6 years)
Population: Health Status | [underlined: Included]:; - Studies done in generally healthy populations; [underlined: Excluded:]; - Studies that exclusively enroll subjects with a disease or with the health outcome of interest (intermediate or endpoint health outcomes); - Studies done in hospitalized or malnourished subjects; - Studies exclusive to pre-term babies (gestational age <37 weeks) or babies that are small for gestational age (<2500g) | [underlined: Included]:; - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease will be included; - Studies that enroll [underlined: some] participants:; - º diagnosed with a disease;; - º diagnosed with a disease, disorder, or condition that affects feeding/eating or growth (e.g., autism spectrum disorder, attentiondeficit/hyperactivity disorder, eating disorder, cleft palate);; - º with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - º born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age; † Gestational age <37 weeks and 0/7 days; ‡ Birth weight <2500g; - º and/or hospitalized for an illness, injury or surgery; [underlined: Excluded:]; - Studies that [underlined: exclusively] enroll participants:; - º diagnosed with a disease;^§^; § Studies that exclusively enroll participants with obesity will be included; - º diagnosed with a disease, disorder, or condition that affects feeding/eating or growth (e.g., autism spectrum disorder, attentiondeficit/hyperactivity disorder, eating disorder, cleft palate);; - º with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; - º born preterm,^†^ with low birth weight,^‡^ and/or small for gestational age;; - º and/or hospitalized for an illness, injury, or surgery^**^; ** Studies that exclusively enroll participants post-cesarean section will be included | Inclusion and exclusion criteria for diagnosis of conditions affecting feeding/eating were specified
Intervention/exposure | [underlined: Included]:; Repeated exposure to a food:; - Length of Exposure Period; - Frequency of Exposure, Number of exposures; - Type of Repeated Exposure; [underlined: Excluded]:; - Exclude if doesn’t meet inclusion criteria | [underlined: Included]:; - Repeated exposure to target food(s): child is exposed to a target food/food-type multiple times; - Repeated exposure may address:; - º Number of exposures: times target food is exposed; - º Duration of exposure period; - º Frequency or number of exposure (per unit of time; per day, per week etc.); - º Type of repeated exposure:; - ▪ Taste and non-taste sensory exposure (smell, tactile, visual); - ▪ Single food: A single target food is presented during each exposure period; - ▪ Multiple foods: More than 1 target food is presented during exposure period; - A single target food is presented within an exposure session; the target food may differ from session to session; - Child is exposed to multiple target foods within each exposure session; - Multi-component interventions in which the isolated effect of repeated food exposure on food acceptance is provided or can be determined despite multiple components; [underlined: Excluded]:; - Multi-component intervention in which the isolated effect of repeated food exposure on food acceptance is not provided or cannot be determined due to multiple components; - Food or flavor exposure in utero or via breastmilk; - Exposure to a taste and flavor (e.g., salty, bitter, sweet) | Inclusion and exclusion criteria for multicomponent interventions was added to address directness; Inclusion criteria was modified to include interventions assessing repeated non-taste sensory exposure to food; Exclusion criteria to clarify the exclusion of studies that assess food or flavor exposure in utero and breastmilk was added.; Exclusion criteria was modified to exclude studies that focus on exposure to taste and flavor or nutrient rather than food
Comparator | [underlined: Included]:; - Pre-exposure versus post-exposure (within subject); - No exposure versus exposure (between subjects); [underlined: Excluded]:; - N/A | [underlined: Included]:; - Pre-exposure versus post-exposure (within-subject); - No exposure versus exposure (between subjects); - Taste exposure versus non-taste exposure (between subjects); [underlined: Excluded]:; - N/A | Taste and non-taste exposure was added as comparator due to revised intervention criteria to include non-taste sensory exposure to food
Outcomes | [underlined: Included]:; - Amount of target food (exposed food) consumed, as measured or reported by parent; - Amount of novel food (non-exposed food) consumed, as measured or reported by parent; - Duration of feeding of target or novel food during infant-led feeding paradigm; - Facial response (expressions made during feeding of target or novel food); - Mother’s perception of infants’ enjoyment of the target or novel food; [underlined: Excluded]:; - Exclude if doesn’t meet inclusion criteria | [underlined: Inclded]:; - Acceptance of food as measured by; - º Amount of target or novel food consumed as measured by research staff or reported by caregiver; - º Length of feeding of target or novel food during infant-led feeding paradigm; - º Facial response (expressions made during feeding of target or novel food); - º Caregiver or investigator’s perception of infants’ enjoyment of the target or novel food; - º Willingness to try/taste; - º Hedonic responses; - º Child’s verbal indication of liking of food; [underlined: Excluded]:; - Acceptance to taste and flavor (e.g., sweet, salty etc.) versus food; - Nutrient intake (e.g., sodium) | Broadened the outcome by including willingness to try/taste, hedonic responses, and child’s verbal indication of liking of food.; Narrowed the outcome by excluding studies that examine acceptance of nutrient intake (e.g., sodium), and acceptance to taste and flavor (e.g. sweet, salty etc.)
Publication status | [underlined: Included]:; - Studies published in peer-reviewed journals; [underlined: Excluded]:; - Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings | [underlined: Included]:; - Peer-reviewed articles published in research journals; [underlined: Excluded]:; - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings | No change
Language | [underlined: Included]:; - Studies published in English; [underlined: Excluded]:; - Studies published in languages other than English | [underlined: Included]:; - Studies published in English; [underlined: Excluded]:; - Studies published in languages other than English | No change
Country^*^; * In order to determine the inclusion exclusion criteria for country, the Human Development classification was used. This classification is based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups) | [underlined: Included]:; - Studies conducted in Very High, High, Middle, or Low Human Development Countries; [underlined: Excluded]:; - NA | [underlined: Included]:; - Studies conducted in countries classified as high or very high on the Human Development Index the year(s) the intervention/exposure data were collected; [underlined: Excluded]:; - Studies conducted in countries classified as medium or low on the Human Development Index the year(s) the intervention/exposure data were collected | Changed to include only countries classified as high or very high on the Human Development Index to more closely reflect the U.S. population