# Appendix 2 Conclusion statement from the existing systematic review

Table A 2 Conclusion statement from the existing systematic review for the research question: What is the relationship between repeated exposure to foods and food acceptance?

Citation | Conclusion statement and grade
Spill M, Callahan E, Johns K, Shapiro M, Spahn JM, Wong YP, Terry N, Benjamin-Neelon S, Birch L, Black M, Briefel R, Cook J, Faith M, Mennella J, Casavale KO, Stoody E. Repeated Exposure to Foods and Early Food Acceptance: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0401. | Moderate evidence from randomized controlled trials indicates that tasting a single or multiple vegetable(s) or fruit(s) 1 food per day for 8 – 10 or more days is likely to increase acceptability of an exposed food (indicated by an increase in food intake or faster rate of feeding after compared to before the exposure period) in infants and toddlers 4 to 24 months old. The effect of repeated exposure on acceptability is likely to generalize to other foods within the same food category but not to foods from a different food category. This evidence does not address the effect of repeated exposure of foods beyond vegetables and fruits on food acceptability in infants and toddlers. Grade: Moderate