# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NRCT: Non-Randomized Control Trial
RCT: Randomized Control Trial
SEP: Socioeconomic Position
USDA: United States Department of Agriculture