# References of the articles included in the systematic review

1 Amaro-Rivera K, Molina J, Perez CM, Palacios C. Longitudinal Associations between Dietary Patterns and Weight Status in Puerto Rican Infants and Toddlers’ Participants of the WIC Program. P R Health Sci J. 2019;38(2):75–80.31260549
2 Gaffney KF, Kitsantas P, Cheema J. Clinical practice guidelines for feeding behaviors and weight-for-age at 12 months: a secondary analysis of the Infant Feeding Practices Study II. Worldviews Evid Based Nurs. 2012;9(4):234–42. Available at: 10.1111/j.1741-6787.2011.00236.x.22233459
3 Mahoney S, Bryant M, Sahota P, Barber S. Dietary intake in the early years and its relationship to BMI in a bi-ethnic group: the Born in Bradford 1000 study. Public Health Nutr. 2018;21(12):2242–2254. Available at: 10.1017/S1368980018000654.29607793
4 Vandyousefi S, Davis JN, Gunderson EP. Association of infant diet with subsequent obesity at 2-5 years among children exposed to gestational diabetes: the SWIFT study. Diabetologia. 2021;64(5):1121–1132. Available at: 10.1007/s00125-020-05379-y.33495846
5 Berkey CS, Rockett HR, Field AE, Gillman MW, Colditz GA. Sugar-added beverages and adolescent weight change. Obes Res. 2004;12(5):778–88. Available at: 10.1038/oby.2004.94.15166298
6 Blum JW, Jacobsen DJ, Donnelly JE. Beverage consumption patterns in elementary school aged children across a two-year period. J Am Coll Nutr. 2005;24(2):93–8. Available at: 10.1080/07315724.2005.10719449.15798075
7 Carlson JA, Crespo NC, Sallis JF, Patterson RE, Elder JP. Dietary-related and physical activity-related predictors of obesity in children: a 2-year prospective study. Child Obes. 2012;8(2):110–5. Available at: 10.1089/chi.2011.0071.22799510
8 Dong D, Bilger M, van Dam RM, Finkelstein EA. Consumption Of Specific Foods And Beverages And Excess Weight Gain Among Children And Adolescents. Health Aff (Millwood). 2015;34(11):1940–8. Available at: 10.1377/hlthaff.2015.0434.26526253
9 Dubois L, Diasparra M, Bogl LH, . Dietary Intake at 9 Years and Subsequent Body Mass Index in Adolescent Boys and Girls: A Study of Monozygotic Twin Pairs. Twin Res Hum Genet. 2016;19(1):47–59. Available at: 10.1017/thg.2015.97.26810866
10 Field AE, Gillman MW, Rosner B, Rockett HR, Colditz GA. Association between fruit and vegetable intake and change in body mass index among a large sample of children and adolescents in the United States. Int J Obes Relat Metab Disord. 2003;27(7):821–6. Available at: 10.1038/sj.ijo.0802297.12821968
11 Fiorito LM, Marini M, Francis LA, Smiciklas-Wright H, Birch LL. Beverage intake of girls at age 5 y predicts adiposity and weight status in childhood and adolescence. Am J Clin Nutr. 2009;90(4):935–42. Available at: 10.3945/ajcn.2009.27623.19692492
12 Guerrero AD, Mao C, Fuller B, Bridges M, Franke T, Kuo AA. Racial and Ethnic Disparities in Early Childhood Obesity: Growth Trajectories in Body Mass Index. J Racial Ethn Health Disparities. 2016;3(1):129–37. Available at: 10.1007/s40615-015-0122-y.26896112
13 Lambourne K, Washburn RA, Lee J, . A 6-month trial of resistance training with milk supplementation in adolescents: effects on body composition. Int J Sport Nutr Exerc Metab. 2013;23(4):344–56. Available at: 10.1123/ijsnem.23.4.344.23239680
14 Johnson L, Mander AP, Jones LR, Emmett PM, Jebb SA. Is sugar-sweetened beverage consumption associated with increased fatness in children? Nutrition. 2007;23(7–8):557–63. Available at: 10.1016/j.nut.2007.05.005.17616342
15 Kral TV, Stunkard AJ, Berkowitz RI, Stallings VA, Moore RH, Faith MS. Beverage consumption patterns of children born at different risk of obesity. Obesity (Silver Spring). 2008;16(8):1802–8. Available at: 10.1038/oby.2008.287.18535546
16 Libuda L, Alexy U, Sichert-Hellert W, . Pattern of beverage consumption and long-term association with body-weight status in German adolescents-results from the DONALD study. Br J Nutr. 2008;99(6):1370–9. Available at: 10.1017/S0007114507862362.18034911
17 Marshall TA, Curtis AM, Cavanaugh JE, Warren JJ, Levy SM. Child and Adolescent Sugar-Sweetened Beverage Intakes Are Longitudinally Associated with Higher Body Mass Index z Scores in a Birth Cohort Followed 17 Years. J Acad Nutr Diet. 2019;119(3):425–434. Available at: 10.1016/j.jand.2018.11.003.30638821
18 Mrdjenovic G, Levitsky DA. Nutritional and energetic consequences of sweetened drink consumption in 6- to 13-year-old children. J Pediatr. 2003;142(6):604–10. Available at: 10.1067/mpd.2003.200.12838186
19 Newby PK, Peterson KE, Berkey CS, Leppert J, Willett WC, Colditz GA. Beverage consumption is not associated with changes in weight and body mass index among low-income preschool children in North Dakota. J Am Diet Assoc. 2004;104(7):1086–94. Available at: 10.1016/j.jada.2004.04.020.15215766
20 Sakaki JR, Li J, Gao S, . Associations between fruit juice and milk consumption and change in BMI in a large prospective cohort of U.S. adolescents and preadolescents. Pediatr Obes. 2021;16(9):e12781. Available at: 10.1111/ijpo.12781.33648027
21 Sakaki JR, Li J, Melough MM, . Orange juice intake and anthropometric changes in children and adolescents. Public Health Nutr. 2021;24(14):4482–4489. Available at: 10.1017/S1368980020003523.33023713
22 Shefferly A, Scharf RJ, DeBoer MD. Longitudinal evaluation of 100% fruit juice consumption on BMI status in 2-5-year-old children. Pediatr Obes. 2016;11(3):221–7. Available at: 10.1111/ijpo.12048.26110996
23 Skinner JD, Carruth BR. A longitudinal study of children’s juice intake and growth: the juice controversy revisited. J Am Diet Assoc. 2001;101(4):432–7. Available at: 10.1016/S0002-8223(01)00111-0.11320948
24 Striegel-Moore RH, Thompson D, Affenito SG, . Correlates of beverage intake in adolescent girls: the National Heart, Lung, and Blood Institute Growth and Health Study. J Pediatr. 2006;148(2):183–7. Available at: 10.1016/j.jpeds.2005.11.025.16492426
25 Vanselow MS, Pereira MA, Neumark-Sztainer D, Raatz SK. Adolescent beverage habits and changes in weight over time: findings from Project EAT. Am J Clin Nutr. 2009;90(6):1489–95. Available at: 10.3945/ajcn.2009.27573.19864412
26 Wan L, Jakkilinki PD, Singer MR, Bradlee ML, Moore LL. A longitudinal study of fruit juice consumption during preschool years and subsequent diet quality and BMI. BMC Nutr. 2020;6:25. Available at: 10.1186/s40795-020-00347-6.32467768
27 Welsh JA, Cogswell ME, Rogers S, Rockett H, Mei Z, Grummer-Strawn LM. Overweight among low-income preschool children associated with the consumption of sweet drinks: Missouri, 1999-2002. Pediatrics. 2005;115(2):e223–9. Available at: 10.1542/peds.2004-1148.15687430
28 Zheng M, Allman-Farinelli M, Heitmann BL, . Liquid versus solid energy intake in relation to body composition among Australian children. J Hum Nutr Diet. 2015;28 Suppl 2:70–9. Available at: 10.1111/jhn.12223.24548259
29 Zheng M, Rangan A, Olsen NJ, . Substituting sugar-sweetened beverages with water or milk is inversely associated with body fatness development from childhood to adolescence. Nutrition. 2015;31(1):38–44. Available at: 10.1016/j.nut.2014.04.017.25441586
30 Aptekmann NP, Cesar TB. Orange juice improved lipid profile and blood lactate of overweight middle-aged women subjected to aerobic training. Maturitas. 2010;67(4):343–7. Available at: 10.1016/j.maturitas.2010.07.009.20729016
31 Auerbach BJ, Littman AJ, Krieger J, . Association of 100% fruit juice consumption and 3-year weight change among postmenopausal women in the in the Women’s Health Initiative. Prev Med. 2018;109:8–10. Available at: 10.1016/j.ypmed.2018.01.004.29330029
32 Bes-Rastrollo M, van Dam RM, Martinez-Gonzalez MA, Li TY, Sampson LL, Hu FB. Prospective study of dietary energy density and weight gain in women. Am J Clin Nutr. 2008;88(3):769–77. Available at: 10.1093/ajcn/88.3.769.18779295
33 Castellana F, Zupo R, Bortone I, . Traditional Old Dietary Pattern of Castellana Grotte (Apulia) Is Associated with Healthy Outcomes. Nutrients. 2020;12(10). Available at: 10.3390/nu12103097.
34 Chen L, Appel LJ, Loria C, . Reduction in consumption of sugar-sweetened beverages is associated with weight loss: the PREMIER trial. Am J Clin Nutr. 2009;89(5):1299–306. Available at: 10.3945/ajcn.2008.27240.19339405
35 Duffey KJ, Gordon-Larsen P, Steffen LM, Jacobs DR, Jr., Popkin BM. Drinking caloric beverages increases the risk of adverse cardiometabolic outcomes in the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. 2010;92(4):954–9. Available at: 10.3945/ajcn.2010.29478.20702604
36 Drapeau V, Després JP, Bouchard C, . Modifications in food-group consumption are related to long-term body-weight changes. Am J Clin Nutr. 2004;80(1):29–37. Available at: 10.1093/ajcn/80.1.29.15213024
37 Ferreira-Pego C, Babio N, Bes-Rastrollo M, . Frequent Consumption of Sugar- and Artificially Sweetened Beverages and Natural and Bottled Fruit Juices Is Associated with an Increased Risk of Metabolic Syndrome in a Mediterranean Population at High Cardiovascular Disease Risk. J Nutr. 2016;146(8):1528–36. Available at: 10.3945/jn.116.230367.27358413
38 Funtikova AN, Subirana I, Gomez SF, . Soft drink consumption is positively associated with increased waist circumference and 10-year incidence of abdominal obesity in Spanish adults. J Nutr. 2015;145(2):328–34. Available at: 10.3945/jn.114.205229.25644355
39 Halkjaer J, Tjonneland A, Overvad K, Sorensen TI. Dietary predictors of 5-year changes in waist circumference. J Am Diet Assoc. 2009;109(8):1356–66. Available at: 10.1016/j.jada.2009.05.015.19631041
40 Hollis JH, Houchins JA, Blumberg JB, Mattes RD. Effects of concord grape juice on appetite, diet, body weight, lipid profile, and antioxidant status of adults. J Am Coll Nutr. 2009;28(5):574–82. Available at: 10.1080/07315724.2009.10719789.20439553
41 Hosseinpour-Niazi S, Aghayan M, Mirmiran P, Azizi F. Does weight change modify the association between the consumption of sugar-sweetened beverages and 100% fruit juice and the risk of metabolic syndrome? Clin Nutr. 2021;40(10):5261–5268. Available at: 10.1016/j.clnu.2021.08.017.34534895
42 Konieczna J, Romaguera D, Pereira V, . Longitudinal association of changes in diet with changes in body weight and waist circumference in subjects at high cardiovascular risk: the PREDIMED trial. Int J Behav Nutr Phys Act. 2019;16(1):139. Available at: 10.1186/s12966-019-0893-3.31882021
43 Mozaffarian D, Hao T, Rimm EB, Willett WC, Hu FB. Changes in diet and lifestyle and long-term weight gain in women and men. N Engl J Med. 2011;364(25):2392–404. Available at: 10.1056/NEJMoa1014296.21696306
44 Pan A, Malik VS, Hao T, Willett WC, Mozaffarian D, Hu FB. Changes in water and beverage intake and long-term weight changes: results from three prospective cohort studies. Int J Obes (Lond). 2013;37(10):1378–85. Available at: 10.1038/ijo.2012.225.23318721
45 Rautiainen S, Wang L, Lee IM, Manson JE, Buring JE, Sesso HD. Higher Intake of Fruit, but Not Vegetables or Fiber, at Baseline Is Associated with Lower Risk of Becoming Overweight or Obese in Middle-Aged and Older Women of Normal BMI at Baseline. J Nutr. 2015;145(5):960–8. Available at: 10.3945/jn.114.199158.25934663
46 Romaguera D, Angquist L, Du H, . Food composition of the diet in relation to changes in waist circumference adjusted for body mass index. PLoS One. 2011;6(8):e23384. Available at: 10.1371/journal.pone.0023384.21858094
47 Schulze MB, Manson JE, Ludwig DS, . Sugar-sweetened beverages, weight gain, and incidence of type 2 diabetes in young and middle-aged women. JAMA. 2004;292(8):927–34. Available at: 10.1001/jama.292.8.927.15328324
48 Shenoy SF, Poston WS, Reeves RS, . Weight loss in individuals with metabolic syndrome given DASH diet counseling when provided a low sodium vegetable juice: a randomized controlled trial. Nutr J. 2010;9:8. Available at: 10.1186/1475-2891-9-8.20178625
49 Silver HJ, Dietrich MS, Niswender KD. Effects of grapefruit, grapefruit juice and water preloads on energy balance, weight loss, body composition, and cardiometabolic risk in free-living obese adults. Nutr Metab (Lond). 2011;8(1):8. Available at: 10.1186/1743-7075-8-8.21288350
50 Siqueira JH, Pereira TSS, Moreira AD, . Consumption of sugar-sweetened soft drinks and risk of metabolic syndrome and its components: results of the ELSA-Brasil study (2008-2010 and 2012-2014). J Endocrinol Invest. 2023;46(1):159–171. Available at: 10.1007/s40618-022-01895-3.35963981
51 Guilloty NI, Soto R, Anzalota L, Rosario Z, Cordero JF, Palacios C. Diet, Pre-pregnancy BMI, and Gestational Weight Gain in Puerto Rican Women. Matern Child Health J. 2015;19(11):2453–61. Available at: 10.1007/s10995-015-1764-4.26100133
52 Alderete TL, Wild LE, Mierau SM, . Added sugar and sugar-sweetened beverages are associated with increased postpartum weight gain and soluble fiber intake is associated with postpartum weight loss in Hispanic women from Southern California. Am J Clin Nutr. 2020;112(3):519–526. Available at: 10.1093/ajcn/nqaa156.32597935