# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between 100% juice consumption and growth, body composition, and risk of obesity?”, with the following conclusion statements.^†^ The grades reflect the strength of the evidence underlying the conclusion statements.

† A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. It does not draw implications and should not be interpreted as dietary guidance.

### Infants and young children^‡^ ‡ Fisher JO, Abrams SA, Andres A, . Complementary Feeding and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR18

A conclusion statement cannot be drawn about the relationship between 100% juice consumption by infants and young children, up to age 24 months, and outcomes related to growth patterns, body composition, and risk of obesity during childhood because of substantial concerns with consistency and precision in the body of evidence. (Grade: Grade Not Assignable)

### Children and adolescents^§^ § The 2025 Dietary Guidelines Advisory Committee developed and graded this conclusion statement based on review of the totality of evidence in infants, children, and adolescents. Due to the lack of evidence in infants and young children, up to 24 months, and issues with its consistency, precision, risk of bias and generalizability, the conclusion statement primarily refers to children and adolescents (2 up to 19 years).

100% juice consumption by children and adolescents is not associated with growth, body composition and risk of obesity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

### Adults and older adults

100% juice consumption by adults and older adults is not associated with body composition. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

100% juice consumption by adults and older adults may not be associated with weight gain. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

### Individuals during pregnancy and postpartum

A conclusion statement cannot be drawn about the relationship between 100% juice consumption during pregnancy and adequacy of gestational weight gain because there is not enough evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between 100% juice consumption during postpartum and postpartum weight change because there is not enough evidence available. (Grade: Grade Not Assignable)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on 100% juice consumption and growth, body composition, and risk of obesity.

1. Future studies should report multiple measures of growth and risk of obesity to strengthen the evidence base (e.g., age- and sex-standardized measures of weight, incidence of obesity).
2. Increase the amount and representation of research being conducted. More studies in older adults, and more research in individuals during pregnancy and postpartum, are needed. Representation of minoritized racial and/or ethnic groups and in people of varying socioeconomic position is currently lacking.
3. Measure consumption of 100% juice with greater specificity, such that 100% juice can be assessed separately from beverages such as juice drinks or juice with added sugar.
4. Future publications from observational studies should better control for confounding factors, such as race and/or ethnicity and socioeconomic position, that may impact the relationship between 100% juice consumption and growth, body composition, and risk of obesity.
5. Specify and separate 100% fruit juice from 100% vegetable juice, in order to clarify the effects of different types of 100% juice.

Table 11 Evidence examining the relationship between 100% juice consumption in infants, children, and adolescents and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
Amaro-Rivera, 2019 ^1^; Prospective Cohort Study, Puerto Rico WIC Clinic, Puerto Rico; Analytic N=68 (Excluded participants lost to follow-up); Participant Characteristics; - Race/ethnicity: 100% Hispanic; - Maternal education: ≤High school: 32.5%, >High school: 67.5%; - Other SEP measure(s): WIC participation: 100%; - Maternal age: Parent’s age: <30 y: 55.8%, ≥30 y: 44.2%; - Milk feeding practices: Exclusively BF for ≥1 mo: 51%, Ever FF: 70.1%; - Child sex (female): 47%; - Gestational age: NR | Exposure: 100% juice intake (continuous; 1 y change DQIS juice component score); Comparator: Fruit juice intake (continuous; DQIS juice component score); [underlined: Exposure assessment method and timing]:; - Interviewer-administered questionnaire completed by caregivers. Diet Quality Index Score based on FFQ; Amounts consumed: NR; - 0-5 mo, 8-11 mo, 12-36 mo; Study beverage intake:; - 32.5% consumed juice at 1-5 mo; Outcomes and assessment methods:; - At 11-36 mo (Median: 21 mo, 11-23 mo: 61.0%, 24-36 mo: 39.0%); - Weight status assessed using WHO age- and sex-specific WLZ growth charts. Relative risk for WLZ at follow-up (≥1 vs <1). Underweight defined as WLZ ≤-2 SD. Healthy weight status defined as WLZ >-2 and <1 SD. Risk of overweight defined as WLZ 1-<2. Overweight or obesity defined as WLZ ≥2 SD. | [underlined: Risk of Overweight/Obesity], Log-binomial regression, RR (95% CI); 100% Juices score increase:; 1.15 (0.98, 1.34) | TEI adjusted: No; Confounders accounted for:; - SEP, sex, milk feeding practices, baseline anthropometry; Confounders NOT accounted for:; - race/ethnicity, gestational age; Additional model adjustments:; WLZ at baseline; Limitations:; - Not all key confounders accounted for; - High attrition (~74%); - Wide age range for outcome (11-36 mo); Funding sources:; University of Puerto Rico Central Administration Grant; Capacity Advancement in Research Infrastructure; National Institute on Minority Health and Health Disparities
Berkey, 2004^5^; PCS, Growing Up Today Study (GUTS), U.S.; Analytic N=11,634; Participant characteristics at baseline: children and adolescents; - Age: Range: 9-14y; - Female: 57%; - Race/ethnicity: White: 95%; - SEP: NR; - Anthropometry: Overweight (>85th percentile CDC BMI charts): boys:; 23.2%; girls: 17.5%;; Very lean (<10th percentile): boys:; 7.2%; girls: 8.6%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Boys, Mean~2290 kcal/d; Girls, Mean~2050 kcal/d; Study beverage intake at baseline:; Mean servings/d (serving size not specified); Apple juice: Boys: ~0.40 svg/d; Girls: ~0.41 svg/d; Orange juice: Boys: ~0.45 svg/d; Girls: ~0.40 svg/d; Inclusion criteria: offspring of Nurses’ Health Study II participants; ages 9-14 at baseline (1996);; Excluded: any height >3 SD beyond gender-age-specific mean height (0.46% excluded); any 1-y height change which declined by >1 inch or increased by >3 SD above mean change (1.65% excluded); BMI < 12.0 kg/m2; BMI >3 SD above or below gender-age-specific mean (0.87% excluded); | Exposure: Fruit juices (orange juice and apple/other juices); Other exposures: Milk, SSB, LNCSB; Comparator: juice intake (continuous); Exposure Assessment Methods and Timing: Self-administered semi-quantitative, validated FFQ for older children and adolescents; Represents intake during previous year At baseline, 1y follow-up, 2y follow-up; Outcome Assessment Methods and Timing: BMI from height and weight self-reported by children with measuring instructions and suggestion to ask someone for help provided (all have mothers who are nurses in NHSII) At baseline, 1y, & 2y follow-ups | [underlined: BMI change over 1y], kg/m2, β (SE), Linear regression; Per 1y svg/d increase:; Not adjusted for TEI; Boys: 0.033 (0.023), P=0.148; Girls: −0.018 (0.020), P=0.361; Adjusted for TEI; Boys: 0.017 (0.024), P=0.488; Girls: −0.021 (0.021), P=0.325 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, diet quality (other beverage intake (sugar added, diet soda)); - Other: Tanner stage, menarche (girls), height growth, milk type (whole/2%/1%/nonfat/soy), inactivity; Limitations:; - Did not account for key confounders: SEP; - Not all key confounders accounted for; Differences in attrition (children lost to follow-up were older and had higher sugar added beverage intake and lower milk intake at baseline); selfreported outcome data; no preregistered data analysis plan; Funding:; NIH; Boston Obesity Nutrition Research Center Grant; CDC; Economic Research Service of the USDA; Kellogg’s
Blum, 2005^6^; PCS, U.S.; Analytic N=166; Participant characteristics at baseline: Children; - Age: Mean (SD): 9.3 (1.0); Range: 3rd-5th grade; - Female: 55%; - Race/ethnicity: White: 94%; - SEP: NR; - Anthropometry: BMI z-score, Mean=0.47, SD=1.0; Height, Mean=139.4 cm, SD=7.9; Weight, Mean=35.7 kg, SD=8.1; - Physical activity: NR; - Smoking: NR; - Diet quality: SSB intake, mean (SD): 7.4 (9.3) oz/d; - TEI: Mean=1957.7 kcal/d, SD=575.3; Study beverage intake at baseline:; Mean (SD): 2.1 (4.4) oz/d; Inclusion criteria: children in grades 3-6; baseline and 2y measurements; Excluded: outlier values (>2.5 SD) on change in BMI z-score (n=2) | Exposure: 100% juice; Other exposures: Milk, SSB, LNCSB; Comparator: juice intake (continuous, oz/d); Exposure Assessment Methods and Timing: 24-hr recall with two interviews per 24-hr period; parents of random sub-sample called to verify consumption at home; Represents intake during past 24-hr on a school day; Baseline, 2y; Outcome Assessment Methods and Timing: Weight and height measured by study staff BMI z-score calculated (CDC age and gender specific) from height and weight; Overweight: BMI z-score ≥1.0; Normal weight: BMI z-score<1.0; Baseline, 2y | [underlined: Change in 100% juice intake for Change-in-BMI z-score subgroups], oz/d; ANOVA, Mean (SD):; Unadjusted analysis; Within group differences: (t-tests); Normal weight at baseline & 2y, n=99: −0.6 (6.4), NS; Overweight at baseline & 2y, n=48; −0.9 (5.6), NS; Gained weight (Normal weight at baseline;; Overweight at 2y), n=11: −0.5 (4.4), NS; Lost weight (Overweight at baseline; Normal weight at 2y), n=6: 2.3 (5.5), NS; Between group differences (ANOVA): All NS; [underlined: BMI z-score], Linear Regression; Increase per oz/d increase in baseline intake: P=NS, Data: NR | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline, diet quality (SSB intake); - Other: Baseline beverage intakes (milk, 100% juice, LNCSB, SSB), 2y follow-up beverage intakes; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, physical activity; - Not all key confounders accounted for; Single 24-hr recall used to assess intake; impact of high level of missing data on analyses unclear; no preregistered analysis plan; Funding:; NR
Carlson, 2012^7^; PCS, MOVE Project (RCT), U.S.; Analytic N=254; Participant characteristics at baseline: Children; - Age: Mean (SD): 6.7 (0.7) y; - Female: 56%; - Race/ethnicity: 48% Latino, 39% non-Hispanic white; - SEP: Parent with college degree: 41%; - Anthropometry: BMI: ≥85th% 20%, ≥95th% 15%; Body Fat %, Mean (SD)=29.9 (8.7); - Physical activity: 4.35 (2.00) days/wk; - Smoking: NR; - Diet quality: Mean (SD); High fat foods: 3.49 (1.66) foods/d Fruits and vegetables: 3.9 (1.68) servings/d; Fast food/restaurants: 1.67 (1.16) times/wk; Meals in front of TV: 1.72 (2.06) times/wk; Breakfast as a family: 3.02 (2.08) days/wk; Dinner as a family: 5.10 (1.53) days/wk; - TEI: NR; Study beverage intake at baseline:; Mean (SD): 0.60 (0.56) svg/d; Inclusion criteria: participants in control group of the MOVE Project (no obesity-related intervention); age 6-7y at baseline; Excluded: living in a foster or group home; medical and/or psychological condition that affected diet, physical activity, growth, or weight; unable to speak, read, and understand either English or Spanish; lost to follow-up; change in % body fat by ≥5 SD from the mean change | Exposure: 100% fruit or vegetable juice (svg = 8 oz); Other exposures: SSB; Comparator: Juice intake (continuous; svg/d); Exposure Assessment Methods and Timing: Unvalidated survey completed by parents; represents usual dietary behavior; Baseline, 2y; Outcome Assessment Methods and Timing: Height and weight measured by trained staff. Age- and gender-specific BMI percentiles and z-scores calculated using CDC growth charts. Percent body fat measured using bioelectrical impedance analysis and Schaefer equation Baseline, 2y | [underlined: BMI z-score over 2y], β (95% CI), Linear regression; Change per svg/d increase: −0.04 (−0.21, 0.13), P=0.631; [underlined: Percent Body Fat over 2y], Linear regression, β (95% CI); Change per svg/d increase: −1.06 (−2.70, 0.57), P=0.202 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (parent education); - Other: Baseline height; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity, diet quality; - Not all key confounders accounted for; Exposure assessment tool not validated; No preregistered data analysis plan; Funding:; NIDDK
Dong, 2015^8^; PCS, Avon Longitudinal Study pf Parents and Children (ALSPAC), U.K.; Analytic N=4,646; Participant characteristics at baseline: Children; - Age: Mean: 8y; - Female: 49%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean: 16.2; BMI z-score, Mean: 0.1; - Physical activity: Mean (SD): 22.9 min/d (15.4) (at age 11y); - Smoking: NR; - Diet quality: Mean (SD), g/d; Fruit: 80; Vegetables: 74; Whole grains: 12; - TEI: NR; Study beverage intake at baseline: grams/d, mean (SD):; 7y: 94.4 (138.1); 10y: 124.0 (154.7); 13y: 164.7 (208.2); Inclusion criterion: Complete dietary and anthropometric data at 7y, 10y, and 13y | Exposure: Fruit juices; Other exposures: Milk, SSB, LNCSB; Comparator: Juices (continuous; g/d): Per 100 g/d change over 3y, Per 100 g/d average across 3y; Exposure Assessment Methods and Timing: Three-day food diary, child report with help from parent; Represents current intake; Ages 7y, 10y, 13y; Outcome Assessment Methods and Timing: Height and weight measured by study personnel Calculated UK age and sex adjusted; BMI z-score to represent adiposity; Excessive weight gain: increase in adiposity over 3y compared to reference group; BMI converted to g for interpretation (assumes 0.01 increase in BMI z-score = 50g); Ages 7y, 10y, 13y | [underlined: Excess weight gain (g) (BMI z-score) over 3y], per 100 g/d increase (change) or per 100 g/d intake (average), Mean, linear regression; Juice intake, continuous Change: β: 10, P=NS; Average: β: −15, P=NS; Boys (n=2155); Change: β: 5, P=NS; Girls (n=2193); Change: β: 20, P=NS; 7-10y period; Change: β: 6, P=NS; 10-13y period; Change: β: 25, P=NS | Model adjustments:; - TEI: no; - Key confounders: Sex, age, SEP (highest education level of child’s mother), physical activity; - Other: Pubertal status (Tanner stage); Limitations:; - Did not account for key confounders: Race and/or ethnicity, anthropometry at baseline, diet quality; - Not all key confounders accounted for; No info on missing data; no preregistered data analysis plan; Funding:; NR
Dubois, 2016^9^; PCS, Quebec Newborn Twin Study, Canada; Analytic N=304; Participant characteristics at baseline: Monozygotic (MZ) twin children; - Age: Mean (SD): 9y (0.6); - Female: 55%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean (SD): 16.5 kg/m2 (2.5); - Physical activity: NR; - Smoking: NR; - Diet quality: Food group intake, kcal/d, % of energy intake; Vegetables: 98, 5%; Fruit & fruit juice: 156, 9%; Whole grain: 86, 5%; Data for other food groups and macronutrients available in paper; - TEI: Kcal/d, Mean (SD): 1,814 (393); Study beverage intake at baseline: Juice intake, Mean (SD): 79.51 (83.26) kcal/d; Excluded: dietary data misreporting (Energy Intake:Basal Metabolic Rate ratios of <0.96 and >2.49) | Exposure: Fruit juice (kcal/d, % of total energy); Other exposures: Milk, SSB; Comparator: Fruit juice (kcal), continuous; Exposure Assessment Methods and Timing: 24-hr recall performed by registered dietitians; Represents usual intake; Baseline (9y); Outcome Assessment Methods and Timing:; Height and weight self-reported except at baseline (measured); Intrapair difference (MZ twins) in BMI; Discordant twins defined as ≥2 BMI units between pairs at least once at 9, 12, 13, and/or 14y; Ages 9y, 12y, 13y, 14y | [underlined: Correlation between intrapair differences in intake at 9y (kcal or % energy) and intrapair differences in BMI in subsequent yrs];; Spearman correlation; Fruit juice intake, continuous; All: kcal; % energy; 12y (n=238): −0.14, NS; −0.15, NS; 13y (n=226): −0.17, P<0.05; −0.14, NS; 14y (n=212): −0.10, NS; −0.14, NS; Change 9-14y (n=210): −0.21, P<0.05; −0.21, P<0.05; Boys: kcal; % energy; 12y (n=102): −0.13, NS; −0.17, NS; 13y (n=96): −0.28, NS; −0.24, NS; 14y (n=92): −0.24, NS; −0.24, NS; Change 9-14y (n=92): −0.25, NS; −0.23, NS; Girls: kcal; % energy; 12y (n=136): −0.16, NS; −0.13, NS; 13y (n=130): −0.11, NS; −0.07, NS; 14y (n=120): 0.03, NS; −0.00, NS; Change 9-14y (n=108): −0.18, NS; −0.17, NS; Refer to paper and supplemental data for additional analyses on:; - Comparison of Dietary Intake (at 9 years) Among Leaner and Heavier Twins From Discordant and Concordant MZ Twin Pairs; - Comparison of Dietary Intake at 9 Years Between Discordant MZ Twins for BMI at 9 Years and Older | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, SEP, diet quality; - Other: None; Limitations:; - Did not account for key confounders: Anthropometry at baseline, physical activity; - No info on missing data; no preregistered data analysis plan; Funding:; Fonds Quebecois de la Recherche sur la Societe et la Culture; Fonds de la Recherche en Sante du Quebec; Social Science and Humanities Research Council of Canada; National Health Research Development Program; CIHR; Sainte-Justine Hospital Research Centre; Academy of Finland
Field, 2003^10^; PCS, Growing Up Today Study (GUTS), U.S.; Analytic N=14,918; Participant characteristics at baseline: children and adolescents; - Age: Mean ~12y (range: 9-14y); - Female: 54%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~19 kg/m2; - Physical activity: NR; - Smoking: NR; - Diet quality: Servings/d of fruits and vegetables:; 2 servings: ~22.9%; 3 servings: ~20.3%; 4 servings: ~16.5%; 5+ servings: ~22.9%; - TEI: ~2100 kcal/d; Study beverage intake at baseline: ~0.9 daily servings; Inclusion criteria: children of women in Nurses’ Health Study II, age 9-14y at baseline, completion of at least 2 GUTS questionnaires between 1996-1999 | Exposure: Juice (no other details provided); Other exposures:; Comparator: Juice intake (continuous; svg/d); Exposure Assessment Methods and Timing: Self-administered semi-quantitative, validated FFQ for older children and adolescents; Represents intake during previous year Baseline and annually for 3y (1996-1999); Outcome Assessment Methods and Timing: Height and weight self-reported; BMI calculated. Age- and gender-specific BMI% and BMI z-score calculated based on CDC growth charts. With overweight: BMI between the national 85th and 95th percentile for age and gender; With obesity: BMI >95th percentile; Baseline and annually for 3y (1996-1999) | [underlined: BMI z-score], Annual change: 1996-1999, Conditional linear model, β (95%CI); Girls:; TEI unadjusted: −0.000 (−0.002, 0.001); TEI adjusted: 0.003 (0.001, 0.005); Boys:; TEI unadjusted: 0.000 (−0.002, 0.002); TEI adjusted: 0.002 (0.000, 0.005) | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, anthropometry at baseline, physical activity; - Other: Tanner stage, inactivity; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, diet quality; - Not all key confounders accounted for; exposure not clearly defined, self-reported height and weight; no preregistered data analysis plan; Funding:; CDC; Boston Obesity Nutrition Research Center; NIH; Kellogg Company
Fiorito, 2009^11^; PCS, U.S.; Analytic N=166; Participant characteristics at baseline: Female children; - Age: Mean: 5y; - Female: 100%; - Race/ethnicity: “Predominantly non-Hispanic white”; - SEP: Family income, averaged $50,000-$75,000;; Paternal education, 14.9y (2.7);; Maternal education, 14.8y (2.3); - Anthropometry: Mean (SD): BMI for age percentile, 59.3 (26.6); Body fat %, 20.6 (4.3); Overweight 18%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline:; NR; Inclusion criteria: complete dietary intake and body weight data at ≥4/6 measurement occasions, living with both biological parents, absence of severe food allergies or chronic medical problems affecting food intake, absence of dietary restrictions involving animal products | Exposure: Fruit juice (100% fruit juice); 1 svg=8oz; Other exposures: milk, SSB; Comparator: Fruit juice intake (continuous; 8 oz svg/d); Exposure Assessment Methods and Timing: Three, 24-hr recalls (2 weekdays, 1 weekend day) within 2- to 3-wk period conducted by trained staff using NDS-R software and reported by mother; represents usual intake Baseline; Outcome Assessment Methods and Timing: Body fat % estimated by tricep and subscapular skinfold thickness at age 5, 7, 9, and 11y and DXA scans at age 9, 11, 13 and 15 At 7, 9, 11, 13, 15y | [underlined: Body fat percentage], Linear Regression, standardized regression coefficient; 7y (N=169): 0.02, P=NS; 9y (N=158): 0.02, P=NS; 11y (N=164): 0.03, P=NS; 13y (N=150): 0.00, P=NS; 15y (N=160): −0.02, P=NS | Model adjustments:; - TEI: no; - Key confounders: Sex; - Other: none; Limitations:; - Did not account for key confounders: Age, race and/or ethnicity, SEP, anthropometry at baseline, physical activity, diet quality; - Not all key confounders accounted for; Possible reporting bias (not all outcome measures reported for each beverage type); no preregistered data analysis plan; Funding:; NIH; The National Dairy Council
Gaffney, 2012^2^; Prospective Cohort Study, IFPS II, United States; Analytic N=691 (Excluded participants without weight data from 12 mo survey, with missing data for essential variables, or with biologically impossible observations for WAZ.); Participant Characteristics; - Race/ethnicity: White: 94.8%, Hispanic: 3.6%, Black: 1.6%; - Maternal education: HS or less: 14.6%, Some college: 34.3%, 4-y college or more: 51.1%; - Other SEP measure(s): Household income (% of poverty line): <185%: 24.7%, 185-349%: 31.4%, >349%: 43.8%; - Maternal age: 18-24 y: 10.1%, 25-34 y: 69.6%, >34 y: 20.3%; - Milk feeding practices: BF intensity 6-12 mo: Low (<20% milk feedings from BM): 52.1%, Medium (20-80% milk feedings from BM): 24.3%, High (>80% milk feeding from BM): 23.6%; - Child sex (female): 51%; - Birth weight: 7.65 (1.02) lb; - Gestational age: 100% born ≥35 wk | Exposure: Juice intake intensity over 6-12 mo (1 juice feeding/2 d, >1 juice feeding/2 d); Comparator: No juice intake (categorical); [underlined: Exposure assessment method and timing]:; - Maternal questionnaire; - 6, 7, 9, 10, and 12 mo; Study beverage intake:; - 0: 21.3%, 1 per 2 d: 35.2%, >1 per 2 d: 43.6%; Outcomes and assessment methods:; - At 12 mo; - Maternal report of weight and age at most recent doctor’s visit. WAZ calculated using age and gender-specific growth reference data from CDC. | [underlined: WAZ], Multiple regression, β (SE); [underlined: 1 juice feeding/2 d]:; 0.25 (0.110), p=0.049; [underlined: >1 juice feeding/2 d]:; 0.21 (0.110), p=0.25 | TEI adjusted: No; Confounders accounted for:; - SEP, sex, milk feeding practices, baseline anthropometry; Confounders NOT accounted for:; - race/ethnicity, gestational age; Additional model adjustments: Bottle-to-bed behavior, BF intensity in late infancy, birth weight, mother’s smoking status, weight gain during pregnancy, mother’s age, mother’s pregravid BMI, mother’s education, mother’s race/ethnicity, household income, introduction to complementary foods; Limitations:; - Not all key confounders accounted for; - No information on funding; - High loss to follow-up (85.9%); Funding sources:; NR
Guerrero, 2016^12^; PCS, Early Childhood Longitudinal Study-Birth Cohort (ECLS-B), U.S.; Analytic N=15,418; Participant characteristics at baseline: Children; - Age: Mean (SD): ~53 (4.1) mo (Range: 44-64.8 mo); - Female: 49%; - Race/ethnicity: White: 43%; Black: 16%; Asian: 11%; Native American: NR; Latino: 20%; Hispanic: NR; Non-Hispanic: NR; Other: 10%; 9% Spanish-speaking; - SEP: 79% lived in 2-parent households; Income: ~24% below fed poverty level; Maternal education: 21% High school, 27% College, 31% ≥Bachelor; Mother’s acculturation (# years in US), mean (SD): 27.6 (10.4)y; - Anthropometry: Mean BMI ~16.5 kg/m2; ~47% with overweight or obesity at baseline; - Physical activity: NR; - Smoking: NR; - Diet quality: Consumption in last week (% Yes); Data from n=7696 included at 48-mo wave (baseline) Any soda: 71.3%; Any fast food: 75.4%; Fruit 7 times/wk: 71.7%; Vegetables 7 times/wk: 68.4%; - TEI: NR; Study beverage intake at baseline:; Any juice in past week (age 48mo): ~92%; Inclusion criteria: non-probability birth sample drawn in 2001; complete data on weight and height; mothers were able to be interviewed; Excluded: serious birth defects (such as spina bifida or heart defects); death before 5y | Exposure: 100% Fruit juice intake; Other exposures: SSB; Comparator: 100% Fruit juice intake, categorical: Any intake in the last 7d vs. No intake in the last 7d; Exposure Assessment Methods and Timing: Parental interview: “Was 100% fruit juice consumed in past 7d? Yes/No” 48, 60, and 72 mo; Outcome Assessment Methods and Timing: Height and weight obtained by trained researchers using standardized procedures and equipment. Age- and sex-specific BMI percentiles calculated using 2000 CDC growth charts; Overweight: BMI 85th-<95th percentile; Obesity: BMI ≥95% percentile 48, 60, and 72 mo | [underlined: BMI across 2y follow up], Hierarchical linear modeling, β (SE); No juice (ref) vs 100% fruit juice within 7d: −0.101 (0.053), NS; By race: No juice (ref) vs 100% fruit juice within 7d; β (SE); White: −0.142 (0.070), P<0.05; Black: −0.082 (0.197), NS; Asian: 0.277 (0.156), NS; Hispanic-English: −0.226 (0.0207), NS; Hispanic-Spanish: −0.021 (0.203), NS | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, socioeconomic position, diet quality (soda intake, daily servings of fruits and vegetables); - Other: Birth weight, breastfeeding during infancy; Limitations:; - Did not account for key confounders: Anthropometry at baseline, physical activity,; - Not all key confounders accounted for; Exposure not well defined (does not account for amount of exposure (just Y/N within 7d); Exposure assessment tool not validated; Baseline, analytic sample sizes, and attrition not clear; No preregistered data analysis plan; Funding:; HHS; University of California’s Institute of Human Development; McCormick Foundation
Lambourne, 2013^13^; RCT-Parallel, U.S.; Baseline N=136, Analytic N=108 (Attrition: 21%); Power: Achieved sample size gives 80% power to detect medium difference (Glass’s delta = 0.75) in FFM among groups with alpha = 0.05, assuming correlation between repeated measures up to 0.60; Participant characteristics at baseline: Adolescents; - Age: Mean: ~13.6y; - Female: 64%; - Race/ethnicity: Minorities: 86%; - SEP: NR; - Anthropometry: Mean ~85th BMI percentile; - Physical activity: Moderate to vigorous physical activity, Mean ~25 min/d; - Smoking: NR; - Diet quality: NR; - TEI: Mean ~1564 kcal/d; Study purpose: to examine the effects of a supervised RT program with daily milk supplementation on weight, fat mass, and fat-free mass in a sample of middle-school students compared to a water control; Excluded: BMI ≤50th ≥99th percentile, resistance training in past 12mo, >3hr/wk of endurance training, were not weight stable (+-4.5kg) past 3mo, used tobacco or weight-altering products or medications that could affet metabolism, had an eating disorder, depression, psychiatric illness, specialized diet regime, food allergies, or lactose intolerance; calcium intake >1,000 mg/d, milk intake >1.5 8oz serv/d | Intervention: 100% fruit juice Participants randomized to a milk, juice, or water group. Juice was isocaloric to milk, and participants had a choice of apple, orange, and/or grape juice daily (in 4-6oz svg, totaling 340-380kcal/d; all groups did resistance training 3d/wk), n=34 (Boys, n=14; Girls, n=20); Other interventions: Resistance training (all groups); Dairy milk; Comparator: Water (24 fl oz/d bottled water per day; resistance training 3d/wk), n=38 (Boys, n=12; Girls, n=26); Duration: 6mo; Study beverage intake at baseline: NR; Compliance: Directly observed by study staff on weekdays and obtained by self-report on weekends; Mean (SD) supplements consumed (total sample): Juice 87.4% (7.2), Water 89.8% (5.8); mean (SD) supplements consumed (per protocol): Juice 89.3% (5.1), Water 91.3% (3.6); Outcome Assessment Methods and Timing: Height and weight measured by trained research staff; BMI percentile calculated using CDC software Waist circumference measured by trained research staff using procedures of Lohman, Roche, and Martorell (1988); Fat Mass (FM), Fat-free mass (FFM), and % body fat: assessed via DXA Baseline, 6mo follow up | [underlined: BMI percentile], Mean (SD), Linear mixed model; By study group: baseline, 6mo change Water: 84.7 (12.7), 0.3 (7.1); Juice: 85.0 (12.7), 1.5 (4.2); Group, P=0.56; Time, P<0.0001; Boys; Water: 85.6 (12.7), −2.0 (4.5); Juice: 85.3 (12.5), 1.5 (4.4); Group, P=0.07; Time, P=0.04; Girls; Water: 84.3 (12.7), 1.4 (7.9); Juice: 84.8 (13.2), 1.5 (4.1); Group, P=0.94; Time, P<0.0001; [underlined: Fat mass], kg, Mean (SD), Linear mixed model; By study group: baseline, 6mo change; Water: 20.9 (10.2), 0.4 (3.6); Juice: 20.1 (10.1), 1.6 (2.5); Group, P=0.33; Time, P<0.0001; Boys; Water: 17.4 (10.6), −1.9 (4.7); Juice: 16.3 (9.1), 1.2 (2.7); Group, P=0.04; Time, P=0.06; Pairwise comparison, P=NS; Girls; Water: 22.5 (9.8), 1.5 (2.5); Juice: 22.8 (10.0), 1.9 (2.3); Group, P=0.85; Time, P<0.0001; [underlined: Fat free mass], kg, Mean (SD), Linear mixed model; By study group: baseline, 6mo change; Water: 41.4 (8.6), 1.7 (2.9); Juice: 44.1 (7.2), 2.7 (1.9); Group, P=0.06; Time, P<0.0001; Boys; Water: 47.9 (9.7), 4.3 (1.4); Juice: 49.3 (7.2), 4.0 (1.3); Group, P=0.99; Time, P<0.0001; Girls; Water: 38.4 (9.7), 0.5 (1.3); Juice: 40.5 (3.7), 1.8 (1.7); Group, P=0.25; Time, P=0.49; Pairwise comparison, P=0.02; [underlined: Percent fat], %, Mean (SD), Linear mixed model; By study group: baseline, 6mo change; Water: 33.5 (11.0), 0 (3.5); Juice: 31.5 (11.4), 0.4 (2.4); Group, P=0.99; Time, P=0.05; Boys; Water: 25.6 (11.0), −2.8 (3.2); Juice: 24.8 (11.5), 0.0 (2.7); Group, P=0.05; Time, P=0.87; Pairwise comparison, P=NS; Girls; Water: 37.2 (11.0), 1.3 (2.9); Juice: 36.2 (9.0), 0.7 (2.2); Group, P=0.22; Time, P=0.01; [underlined: WC], cm, Mean (SD), Linear mixed model; By study group: baseline, 6mo change; Water: 77.3 (9.3), 0.6 (4.2); Juice: 76.7 (8.8), 1.7 (2.9); Group, P=0.20; Time, P=0.67; Boys; Water: 79.0 (10.3), 0.9 (5.2); Juice: 78.5 (8.0), 1.3 (3.7); Group, P=0.21; Time, P=0.85; Girls; Water: 76.6 (8.9), 0.4 (3.8); Juice: 75.4 (9.4), 1.9 (2.2); Group, P=0.25; Time, P=0.49; [underlined: Body mass], kg, Mean (SD), Linear mixed model; By study group: baseline, 6mo change; Water: 62.8 (13.8), 2.3 (2.9); Juice: 64.8 (11.9), 4.2 (3.1); Group, P=0.12; Time, P<0.0001; Boys; Water: 65.1 (13.8), 2.8 (3.3); Juice: 65.9 (11.4), 5.2 (3.1); Group, P=0.14; Time, P<0.0001; Girls; Water: 61.8 (14.0), 2.0 (2.8); Juice: 64.1 (12.5), 3.5 (3.1); Group, P=0.60; Time, P<0.0001 | Model adjustments:; - TEI: no; - Other: Study site; Limitations:; - No information on randomization and concealment of allocation sequence; No preregistered data analysis plan; Funding:; Dairy Research Institute
Johnson, 2007^14^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), Children in Focus (CIF) subsample, UK; Analytic N=5y & 9y (n=521); 7y & 9y (n=682); Participant characteristics at baseline: British children born to ALSPAC participants from 04/1991-12/1992.; - Age: Mean (SD): 5.16y (0.05); - Female: NR; - Race/ethnicity: NR; - SEP: Maternal education and paternal class: Data NR; - Anthropometry: Fat mass at 5y, kg, Mean (SD): 8.47(4.98); Weight at 5y, kg, Mean(SD): 19.52 (2.54); Overweight at 5y (≥95th percentile): 15%; - Physical activity: NR; - Smoking: NA; - Diet quality: Dietary energy density, kJ/g at 5y: 8.52 (1.49); - TEI: TEI at 5y, Mean (SD) 6218 (1393) kJ/d; Misreporting of TEI, TEI / Estimated energy requirements (EER) at 5y, Mean (SD): 1.06 (0.24); Study beverage intake at baseline:; 100% juice intake, Median (IQR); 5y: 0 (0-117) g/d;; 7y: 19 (0-152) g/d; Paper contains beverage intake data at 5y and 7y stratified by maternal education; Excluded: Missing data on diet or body composition | Exposure: Fruit juice (100% fruit juices and concentrates); Other exposures: SSB, milk, LNCSB; Comparator: Different intake level of 100% juice (continuous, g/d or svg/d); Exposure Assessment Methods and Timing: Parent-report, 3-day unweighed dietary records, previously validated using weighed dietary records; 5y, 7y; Outcome Assessment Methods and Timing: Fat mass (kg): DXA; Fat mass index (FMI): Fat mass (kg) / Height (m^5.8); log transformed; Height: valid measure by study staff; Weight: valid measure by study staff; Age: 9.8 (0.15)y | [underlined: Change in fat mass], kg/serving (95% CI), p-value, Linear regression; Change 5y-9y per serving of 100% juice at 5y (n=362):; -0.11 (−0.61, 0.38), p=0.66; Change 7y-9y per serving of 100% juice at 7y (n=471):; 0.25 (−0.08, 0.58), p=0.14; [underlined: FMI quintile], Spearmean correlation coefficient By mean volume of 100% juice consumed (g/d) at age 5y: Data NR, NS; By mean volume of 100% juice consumed (g/d) at age 7y: Data NR, NS | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, socioeconomic position (maternal education, paternal class), anthropometry at baseline, physical activity, smoking, diet quality; - Other: TV watching, parental BMI, fat intake, fiber intake, EI/EER; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - High attrition/missing data; No information on non-completers; No preregistered data analysis plan; Funding:; U.K. Medical Research Council, the Wellcome Trust, and the University of Bristol
Kral, 2008^15^; PCS, U.S.; Analytic N=49; Participant characteristics at baseline: Children; - Age: Mean: ~3y; - Female: 44%; - Race/ethnicity: White: 100%; - SEP: NR; - Anthropometry: BMI z-score, Mean ~ −0.4; WC, Mean ~49.8 cm; - Physical activity: NR; - Smoking: NR; - Diet quality: SSB (oz/d), Mean (SEM); Low risk: 1.8 (1.0); High risk: 2.3 (1.0); - TEI: NR; Study beverage intake at baseline:; Mean ~8.5 oz/d; Inclusion criteria: at either high or low risk of obesity based on maternal pre-pregnancy BMI; food records at ages 3, 4, 5, & 6y | Exposure: Fruit juice (100% juice); Other exposures: Milk, SSB, LNCSB; Comparator: Fruit juice intake (change from 3y to 5y; continuous; kcal/d); Exposure Assessment Methods and Timing: Three day weighed food and beverage record (2 weekdays, 1 weekend day) recorded by primary caregiver; Represents usual intake Baseline, 1y & 2y follow ups; Outcome Assessment Methods and Timing: Waist circumference measured in triplicate at the narrowest part of torso by trained anthropometrists; Height and weight measured in triplicate by trained anthropometrists; BMI z-score calculated using CDC growth charts; Baseline, 1y, 2y, & 3y follow ups | [underlined: BMI z-score change from 5y – 6y], per change in kcal/d from 3y – 5y, B (SE), Linear mixed model:; Data NR, p>0.10; [underlined: WC change from 5y – 6y], per change in kcal/d from 3y – 5y, B (SE), Linear mixed model: Data NR, P=NS | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, diet quality (other beverage intake, including SSB); - Other: change in BMI z-score or waist circumference from ages 3 to 5 years; Limitations:; - Did not account for key confounders: SEP, physical activity; - Not all key confounders accounted for; Baseline n NR and no information on non-completers; No preregistered data analysis plan; Exposure data based on parental weighed food records; Funding:; NIH; General Clinical Research Center; Nutrition Center of the Children’s Hospital of Philadelphia
Libuda, 2008^16^; PCS, Dortmund Nutritional and Longitudinally Designed (DONALD), Germany; Analytic N=244; Participant characteristics at baseline: Children and adolescents; - Age: ~11.9y (range: 9-18y); - Female: 49%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~18.3; Mean percent body fat: ~19%; - Physical activity: NR; - Smoking: NR; - Diet quality: Regular soft drink consumption, mean (SD): Boys: 277 (296) g/d; Girls: 243 (273) g/d; - TEI: ~8200 kJ/d; Study beverage intake at baseline:; Mean (SD): boys: 178 (224) g/d, girls: 180 (236) g/d; Inclusion criteria: completion of at least 4 out of 6 possible annual dietary records; Excluded: potential under-reporting of dietary intake (ratio of reported total energy intake and predicted individual BMR above age- and sex-specific cut-off values of 1.04 for boys and 1.01 for girls (6-13 year old subjects) and of 1.07 for boys and 0.97 for girls (14-18 year old subjects) | Exposure: 100% juice (no other details provided); Other exposures: SSB; Comparator: Fruit juice (continuous; g/d); Exposure Assessment Methods and Timing: 3d weighed dietary records; All foods/bevs before consumption and leftovers were weighed and recorded by the parents, or by the older subjects themselves, on 3 consecutive days; participants chose the 1st day of recording within a given period of time; Baseline, annually for 5y; Outcome Assessment Methods and Timing: Body weight measured to nearest 0·1 kg using an electronic scale. Height was measured in a standing position to the nearest 0·1 cm using a digital telescopic stadiometer. Skinfold thickness: Triceps and subscapular skinfolds measured on right side of body using skinfold caliper. Body fat percentage (%BF): sum of both skinfolds using equations of Slaughter. Sex- and age-independent BMI standard deviation scores (BMI-SDS) calculated using German national reference data: Overweight: BMI values 90th – 97th percentile, Obesity: BMI values > 97th percentile; Baseline, annually for 5y | [underlined: BMI-SDS over 5y follow-up] (β); Boys; Baseline intake*time: 0.033, P=0.310; Change in intake: −0.002, P=0.964; Girls; Baseline intake*time: −0.046, P=0.161; Change in intake: 0.096, P=0.013; [underlined: %Body Fat over 5y follow-up (β)]; Boys; Baseline intake*time: −0.058, P=0.874; Change in intake: −0.121, P=0.756; Girls; Baseline intake*time: −0.265, P=0.426; Change in intake: 0.615, P=0.139 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (maternal education level), anthropometry at baseline; - Other: Time in years after maximal growth velocity (equals years of adolescence) as an indicator for pubertal status, birth weight, maternal BMI; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality; - Not all key confounders accounted for; No preregistered data analysis plan; Funding:; German Federal Ministry of Food, Agriculture and Consumer Protection
Mahoney, 2018^3^; Prospective Cohort Study, Born in Bradford 1000, UK; Analytic N = 779 (Excluded participants with multiple births, missing child dietary data or outcome data, and not of White British or Pakistani ethnicity); Participant Characteristics; - Race/ethnicity: Pakistani: 49%, White British: 38%; - Maternal education: NR; - Other SEP measure(s): NR; - Maternal age: NR; - Milk feeding practices: NR; - Child sex (female): NR; - Birth weight: 3234.15 (521.97) g; - Gestational age: NR | Exposure: Pure fruit juices and baby fruit juices; Comparator: Juice intake (categorical; (Consumer vs non-consumer at 12 mo, ≤ vs > Median at 18 mo)); [underlined: Exposure assessment method and timing]:; - FFQ completed by parents; - 12, 18 mo; Study beverage intake:; - Frequency/wk pure fruit juice (Median, IQR): 12 mo: 0.0 (0.0, 0.5); 18 mo: 7.0 (0.0, 7.0); Outcomes and assessment methods:; - At 36 mo; - Height, weight measured by trained researchers. Age- and sex-adjusted BMI z-score calculated based on WHO 2006 standards. | [underlined: BMI z-score at 36 mo], Multiple regression, β (95% CI); [underlined: Intake at 12 mo]: Consumer vs non-consumer:; -0.05 (−0.20, 0.10), p=0.53; [underlined: Intake at 18 mo]: > vs ≤ 7.0/wk:; -0.07 (−0.21, 0.08), p=0.37 | TEI adjusted: No; Confounders accounted for:; - sex, race/ethnicity, baseline anthropometry; Confounders NOT accounted for:; - SEP, milk feeding practices, gestational age; Additional model adjustments: Ethnicity, gender, birth weight, other key indicator food groups (formula milk; commercial savory baby foods; commercial sweet baby foods; chips, roast and potato shapes; processed meat products; vegetables; fruit; cakes, biscuits, chocolate and sweets; crisps and savory snacks; sugar-sweetened drinks; low-sugar drinks; water); Limitations:; - Not all key confounders accounted for; - Most participant characteristics NR; - High attrition; Funding sources:; NIHR
Marshall, 2019^17^; PCS, Iowa Fluoride and Iowa Bone Development Studies, U.S.; Analytic N=623; Participant characteristics at baseline: Children; - Age: Range: 2-4.7y; - Female: 51%; - Race/ethnicity: Non-Hispanic white: 94%; - SEP: Mother had 4y college degree 45%; Household annual income ≥$60,000 19%; Low 25%, Middle 38%, High 38%; - Anthropometry: BMI, Mean~16.0 kg/m2; BMI z-score, Mean~0.31; - Physical activity: NR; - Smoking: NR; - Diet quality: SSB, oz/d, Median (25th, 75th percentile); Males: 2.7 (1.1, 5.1); Females: 2.6 (1.2, 5.1); - TEI: Median~1360 kcal/d; Inclusion criteria: ≥2 assessments ages 2-8.5y or ≥1 ages 9-17y | Exposure: 100% juice intake (juice drinks were included in this group through age 8.5y, but were assessed separately in later surveys); Other exposures: Milk, SSB, LNCSB; Comparator: Juice intake (continuous; 8 oz/d); Exposure Assessment Methods and Timing: Validated beverage frequency questionnaire; represents previous week’s beverage intakes At 3- to 6-mo intervals: ages 9-10.5, 11-12.5, 13-14.5, and 15-17y. Mean daily beverage intakes were calculated for each subject from all available questionnaires over the time periods preceding clinic examinations (i.e., 9 to 10.5, 11 to 12.5, 13 to 14.5, and 15 to 17 years).; Outcome Assessment Methods and Timing: Height measured without shoes using stadiometer during clinic visits; Weight was measured at clinic visit using a standard physician’s scale; BMIs were calculated from weight and height measures (kg/m2); Age- and sex-specific BMI z-scores calculated 2000 CDC growth charts; At ages 9, 11, 13, 15, 17y | [underlined: BMI z-score], Change through age 17y, per 8 oz/d increase over same period, Linear regression:; β: 0.044, 95% CI: −0.038, 0.125, P=0.29 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP (household income and maternal education), anthropometry at baseline, diet quality (other beverage intake, including SSB); - Other: Protein intake, other beverage intake; Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity; - Not all key confounders accounted for; No information on non-completers; No preregistered data analysis plan; Funding:; NIH; The Roy J. Carver; Charitable Trust; Delta Dental of Iowa Foundation
Mrdjenovic, 2003^18^; PCS, Cornell Summer Day Camp (RCT), U.S.; Analytic N=21; Participant characteristics at baseline: Children and adolescents; - Age: ~8y (range: 6-13y); - Female: 37%; - Race/ethnicity: mostly white, 17% (n=5) from minority groups; - SEP: mostly upper middle-class families; - Anthropometry: BMI ~16.5 kg/m2; - Physical activity: NR; - Smoking: NR; - Diet quality: Sweetened drink consumption, mean (SD): 6-7y: 366 (306) g/day; 7-10y: 233 (234) g/day;; 11-13y: 415 (433); - TEI: ~1618 kcal/d; Study beverage intake at baseline: Mean~120 g/d; Inclusion criteria: “healthy” children with no known food intolerances or allergies; Excluded: children with poor dietary recording | Exposure: Pure or 100% fruit juice (6 oz = 1 serving); Other exposures: SSB; Comparator: Fruit juice intake (categorical; oz/d): 0 (no drink consumed); <6 (1 svg/d); 6-12 (2 glasses or 1 cup); >12 ; >16 oz/d; Exposure Assessment Methods and Timing: Food consumption at camp (during weekdays) was weighed before and after consumption; food consumption at home (weekend) calculated based on recorded amounts by converting home measures into grams. Children served themselves a drink of their choice whenever they wished, but were requested to report the amounts they drank. Daily throughout a 4-8wk follow up; Outcome Assessment Methods and Timing: Height measured without shoes to the nearest cm with a portable field stadiometer; Weight measured to the nearest gram in the morning before breakfast using portable digital scale.; BMI calculated from weight and height.; Baseline, during last week of camp (NR) | [underlined: Weight Gain], kg, Multiple regression, β (SD) Change per oz/d increase:; <6 oz/d: 0.5 (0.4); 6-12 oz/d: Data NR; >12 oz/d: 3.3 (1.95); >16: Data NR; P for trend=0.2 | Model adjustments:; - TEI: yes; - Key confounders: None; - Other:; Limitations:; - Did not account for key confounders: Sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality; - Not all key confounders accounted for; Exposure based on self-report by child; Power analysis NR; Potential selection bias (unclear why 30 of 42 were selected into study); High attrition (30%); Follow-up time NR; Unclear of outcome assessment timing; No preregistered data analysis plan; Funding:; USDA
Newby, 2004^19^ PCS, U.S.; Analytic N=1,345; Participant characteristics at baseline: Low-income preschool children; - Age: Mean (SD): 2.9y (0.7); - Female: 50%; - Race/ethnicity: Native American 11%, Other 6%, White 83%; - SEP: Maternal education, Mean~12.6y; Poverty level: <100%: 55%; 100-133%: 22%; >133-185%: 23%; - Anthropometry: BMI, Mean~16.6 kg/m2; At risk of overweight 14%, Overweight 6%; - Physical activity: NR; - Smoking: NR; - Diet quality: Soda intake: Mean~1.2 oz/d; ≥12 oz/d: ~3%; - TEI: Mean~1747 kcal/d; Study beverage intake at baseline: Mean~10.7 oz/d; ≥12 oz/d: 45%; Inclusion criteria: children seen by North Dakota WIC Program between 1/1/95 and 6/30/98; Excluded: only 1 clinic visit, underweight (based on age- and sexspecific 5th percentile BMI), implausible energy intake (<800 kcal or >3500 kcal/d), unreasonable measures for weight-for height, weightfor-age or height-for-age, “suspicious” change in BMI between visits (< −4 or >4 kg/m2), child breastfeeding at baseline | Exposure: 100% fruit juices (e.g., orange juice, apple juice), ounces/day; Other exposures: Milk, SSB, LNCSB; Comparator: Fruit juice intake (continuous; oz/d); Fruit juice intake (categorical; oz/d): <12 (ref) vs. ≥12; Exposure Assessment Methods and Timing: Validated FFQ; represents dietary intake during previous month; At baseline, follow-up 6-12mo later (mean 8.4mo); Outcome Assessment Methods and Timing: Height measured by trained staff using wall-mounted measuring board. Weight measured by trained staff using standard floor-model beam scale. Age- and sex-specific BMI calculated based on 2000 CDC growth charts. At risk of overweight (BMI 85th to <95th percentile); Overweight (BMI≥95th percentile) At baseline, follow-up 6-12mo later (mean 8.4mo) | [underlined: Weight], Linear regression; Change per oz/d increase, β (SE):; TEI adj: 0.01 (0.01), P=0.23; <12 oz/d (ref) vs. ≥12 oz/d: NS, Data NR; [underlined: BMI], Linear regression; Change per oz/d increase, β (SE):; TEI adj: 0.01 (0.00), P=0.20; <12 oz/d (ref) vs. ≥12 oz/d: NS, Data NR; Estimates remained similar when TEI was omitted from model. (Data NR) | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, SEP (maternal years of education, poverty level), anthropometry at baseline (weight), diet quality (other beverages); - Other: Birth weight, change in height, residence (town or city, rural, reservation, military base); Limitations:; - Did not account for key confounders: Physical activity; - Not all key confounders accounted for; No preregistered data analysis plan; Funding:; USDA; NIH Health Harvard Education Program in Cancer Prevention Control; Boston Obesity Nutrition Research Center
Sakaki, 2021a^21^; PCS, Growing Up Today Study II, U.S.; Analytic N=7,301; Participant characteristics at baseline: children and adolescents; - Age: Mean (SD); Boys: 13.3 (1.8)y; Girls: 13.4 (1.8)y; Range 9-16y; - Female: 55%; - Race/ethnicity: 96% Non-Hispanic White; - SEP: NR; - Anthropometry: BMI, kg/m2, mean (SD); Boys: 20.3 (3.8); Girls: 20.1 (3.6); Overweight/obesity prevalence: 24.6% boys and 17.3% girls; - Physical activity: MET-hr/wk, mean (SD); Boys: 92.1 (66.5); Girls: 69.4 (51.3); - Smoking: NR; - Diet quality: NR; - TEI: Boys: Mean 9736 kJ/d; Girls: Mean 8159 kJ/d; Study beverage intake at baseline:; Orange juice intake (glasses/wk), Mean (SD): Boys 2.6 (3.4); Girls 2.2 (3.0); Inclusion criteria: participants that responded to 2004 baseline questionnaire and 2006 follow-up questionnaire. Excluded from analysis if participant questionnaires had incomplete/invalid values for juice intake, age, weight, height, screen time, extremely low BMI (<12 kg/m2), total daily caloric intake <2092 kJ or >20920 kJ, implausible changes in energy intake between survey years (>8368 kJ change) | Exposure: Orange juice (authors note it is likely 100%); Other exposures: none; Comparator: Categorical (never or <1 glass/mo, 1-3 glasses/mo, 1-6 glasses/wk, ≥1 glass/d); Exposure Assessment Methods and Timing: Semiquantitative FFQ validated; represents usual food and beverage intake over preceding year; contained specific questions on orange juice separate from other beverages or juices. 2004 and 2006; Outcome Assessment Methods and Timing: Height and weight were self-reported by children and used to calculate BMI, BMI%, and HAZ.; BMI% based on 2000 CDC growth charts and used to determine weight status (defined by CDC).; 2004, 2006, and 2008 | [underlined: 2yΔ HAZ by baseline juice intake], adjusted mixed linear regression, Mean (SE); Boys; Never or <1 glass/mo: 0.04 (0.02); 1-3 glasses/mo: 0.08 (0.02); 1-6 glass/wk: 0.05 (0.01); ≥1 glass/d: 0.03 (0.02); P-trend=0.30; Girls; Never or <1 glass/mo: 0.03 (0.01); 1-3 glasses/mo: 0.03 (0.02); 1-6 glass/wk: 0.06 (0.01); ≥1 glass/d: 0.09 (0.02); P-trend=0.02; [underlined: 2yΔ Height (cm) by baseline juice intake], unadjusted mixed linear regression, Mean (SE); Boys; Never or <1 glass/mo: 10.6 (7.4); 1-3 glasses/mo: 10.9 (7.6); 1-6 glass/wk: 10.2 (7.5); ≥1 glass/d: 10.0 (7.4); P-trend=0.02; Girls; Never or <1 glass/mo: 4.9 (6.2); 1-3 glasses/mo: 4.5 (5.9); 1-6 glass/wk: 4.5 (5.7); ≥1 glass/d: 5.2 (6.4); P-trend=0.22; [underlined: 2yΔ BMI percentile by baseline juice intake], adjusted mixed linear regression, Mean (SE); Boys; Never or <1 glass/mo: −0.94 (0.53); 1-3 glasses/mo: −1.68 (0.52); 1-6 glass/wk: −0.81 (0.38); ≥1 glass/d: −1.12 (0.61) p-trend=0.81; Girls; Never or <1 glass/mo: −0.44 (0.36); 1-3 glasses/mo: 0.20 (0.41); 1-6 glass/wk: −0.04 (0.34); ≥1 glass/d: −0.77 (0.62); p-trend=0.49; [underlined: 2yΔ Weight (kg) by baseline juice intake], unadjusted; mixed linear regression, Mean (SD); Boys; Never or <1 glass/mo: 11.7 (7.4); 1-3 glasses/mo: 11.5 (7.6); 1-6 glass/wk: 11.3 (7.4); ≥1 glass/d: 11.1 (6.9); p-trend=0.14; Girls; Never or <1 glass/mo: 6.1 (6.4); 1-3 glasses/mo: 6.1 (6.1); 1-6 glass/wk: 6.0 (5.7); ≥1 glass/d: 6.0 (5.3); p-trend=0.63; [underlined: 2yΔ BMI (kg/m2) by baseline juice intake], unadjusted mixed linear regression, Mean (SD); Boys; Never or <1 glass/mo: 1.5 (2.1); 1-3 glasses/mo: 1.4 (2.3); 1-6 glass/wk: 1.4 (2.3); ≥1 glass/d: 1.5 (1.9); p-trend=0.79; Girls; Never or <1 glass/mo: 1.2 (2.2); 1-3 glasses/mo: 1.3 (2.5); 1-6 glass/wk: 1.2 (1.8); ≥1 glass/d: 1.0 (2.6); p-trend=0.09 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity; - Other: screen time (for BMI percentile analyses); Limitations:; - Did not account for key confounders: socioeconomic position, diet quality; - Only baseline exposure data used in analyses; No information on non-completers; Height and weight were self-reported; No preregistered data analysis plan; Funding:; Florida Department of Citrus
Sakaki, 2021b^20^; PCS, Growing Up Today II, U.S.; Analytic N=8,173; Participant characteristics at baseline: children and adolescents; - Age: Mean (SD): 13.3y (1.81) (Range: 9-16y); - Female: 56%; - Race/ethnicity: >95% non-Hispanic white; - SEP: NR; - Anthropometry: BMI Mean (SD); Boys: 20.3 (3.9); Girls: 20.2 (3.7); - Physical activity: MET-hrs/wk: Mean (SD); Boys: 91.99 (66.02); Girls: 70.35 (52.13); - Smoking: NR; - Diet quality: NR; - TEI: Mean (SD):; Boys: 2324 kcal/d (724);; Girls: 1953 kcal/d (638); Study beverage intake at baseline:; Mean (SD):; Total 100% juice: ~0.64 (0.69) servings/day; Orange juice: ~0.34 (0.46); Other fruit juice: ~0.29 (0.42); Consume any milk at least monthly: 95%; Excluded: missing data on age, race, PA, TEI, or beverage intake at baseline or 2y follow up; implausible energy intake or change in daily intake (n=92), or extremely low BMI (<12kg/m2) (n=64) | Exposure: Total 100% fruit juice intake; orange juice only; apple/other fruit juice only 1 serving = 10 fl oz.; Other exposures: Dairy milk; Comparator: Continuous intake (svg/d); Exposure Assessment Methods and Timing: Child/adolescent semi-quantitative FFQ, validated; Baseline; Outcome Assessment Methods and Timing: Participant self-reported and measured height and weight; 2y & 4y follow up | [underlined: BMI change over 2y], β (SE), p-value, linear regression; Total 100% fruit juice:; Boys: −0.02 (0.04), p=0.59; Girls: −0.10 (0.04), p<0.01; Orange juice:; Boys: 0.03 (0.06), p=0.62; Girls: −0.14 (0.05), p=0.01; Other fruit juice:; Boys: −0.08 (0.07), p=0.22; Girls: −0.07 (0.06), p=0.32 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, total energy intake; - Other:; Limitations:; - Did not account for key confounders: socioeconomic position, diet quality; - Exposure not well defined, Exposure data only measured at baseline; No information on non-completers; BMI was selfreported; No preregistered data analysis plan; Funding:; The Florida Department of Citrus (an executive agency of the state of Florida)
Shefferly, 2016^22^; PCS, Early Childhood Longitudinal Study-Birth Cohort (ECLS-B), U.S.; Analytic N=6,250; Participant characteristics at baseline: Children; - Age: 2y; - Female: 49%; - Race/ethnicity: White: 53.6%; Black: 13.7%; Asian: 2.7%; Hispanic: 25.3%; Other: 4.8%; - SEP: Determined by National Center for Education Statistics based on family income, maternal education, maternal occupation, paternal education, and paternal occupation; divided into quintiles (5=highest SEP; 1=lowest SEP); High 20.7%, Medium high 20.6%, Medium 20.1%, Medium low 19.7%, Low 18.9%; - Anthropometry: Weight status: Normal weight 67.5%, Overweight 15.6%, Obesity 16.9%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: 72% were ‘regular drinkers’ (drank juice at/between meals or snacks); Inclusion criteria: children with birth certificate from 2001; Excluded: age < 24 months; incomplete data on juice intake | Exposure: 100% fruit juice intake (orange, apple, or grape); 1 svg=8oz; Other exposures:; Comparator: Juice intake (categorical; svg/d): Regular drinkers; ≥1; Infrequent/non-drinkers; <1; Exposure Assessment Methods and Timing: Parent interview in the home by trained assessors (or computer at 2y); represents usual intake; Baseline (age 2y), age 4y and 5y; Outcome Assessment Methods and Timing: Height and weight obtained by trained researchers using standardized procedures and equipment. Age- and sex-specific BMI percentiles and z-scores calculated using 2000 CDC growth charts. Weight categories: with normal weight (BMI<85th%), with overweight (BMI 85th-<95th%), and with obesity (BMI≥95th%); Baseline (age 2y), age 4y and 5y | [underlined: Overweight (BMI 85th-95th%),] Logistic regression, OR (95% CI); Change from 2–4y between groups: <1 vs ≥1 svg/d: 1.30 (1.06, 1.59); P=0.0129; Change from 4–5y between groups: <1 vs ≥1 svg/d: 0.86 (0.63, 1.16); P=0.4010; [underlined: Obesity (BMI≥95th%),] Logistic regression, OR (95% CI); Change from 2–4y between groups:; <1 vs ≥1 svg/d: 1.30 (0.93, 1.83); P=0.1293; Change from 4–5y between groups:; <1 vs ≥1 svg/d: 0.80 (0.43, 1.49); P=0.4730; [underlined: BMI z-score], Linear regression, β (SE); Change from 2–4y between groups:; <1 svg/d: 0.030 (0.037); ≥1 svg/d: 0.282 (0.028); P=0.0003; Change from 4–5y between groups:; <1 svg/d: 0.034 (0.031); ≥1 svg/d: 0.020 (0.021); P=0.6778; [underlined: Height z-score], Linear regression, β (SE); Change from 2–4y between groups:; <1 svg/d: 0.410 (0.028); ≥1 svg/d: 0.308 (0.020); P=0.0010; Change from 4–5y between groups:; <1 svg/d: 0.052 (0.020); ≥1 svg/d: 0.071 (0.015); P=0.3670; [underlined: Weight z-score], Linear regression, β (SE); Change from 2–4y between groups:; <1 svg/d: 0.371 (0.032); ≥1 svg/d: 0.432 (0.024); P=0.0550; Change from 4–5y between groups:; <1 svg/d: 0.042 (0.016); ≥1 svg/d: 0.029 (0.012); P=0.4553 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline (baseline z-score (for analyses of change in height, weight, and BMI-z-score)); - Other: Maternal BMI; Limitations:; - Did not account for key confounders: physical activity, diet quality; - Not all key confounders accounted for; Exposure assessment tool not validated; no information on non-completers; No preregistered data analysis plan; Funding:; NIH; Doris Duke Charitable; Foundation Career Development Award
Skinner, 2001^23^; PCS, U.S.; Analytic N=72; Participant characteristics at baseline: Children; - Age: Mean ~27mo; - Female: 49%; - Race/ethnicity: 100% white; - SEP: mostly middle or upper SEP; all parents except 1 mother had some education beyond high school; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Mean: 1406 kcal/d; Study beverage intake at baseline: Mean (SD): 6.8 (6.3) oz/d; 0.51 (0.46) oz/kg; Inclusion criteria: continuous participants in another longitudinal study from 1992-1999; complete or mainly complete data sets | Exposure: 100% juice intake; Comparator: 100% juice intake (continuous); Exposure Assessment Methods and Timing:; Average of 7 sets of 3-day dietary info (One 24hr recall & 2d food records) from 7 interviews with parent (when child was age ~27, ~34, 42, 48, 54, 60 and 72mo); represents usual intake Baseline (mean age 27mo), and every 6mo until age 72mo; Outcome Assessment Methods and Timing: Height measured to nearest 0.1 cm by registered dietitian with a steel tape using a wall or doorway and a square; Weight measured to nearest 0.1 pound by registered dietitian using standard scale. BMI calculated as kg/m2. At baseline (age 27mo), and 4y follow-up (age 72mo). Growth parameters at 72mo were compared to national norms | [underlined: Height], cm, General linear model Change per longitudinal juice intake: Β=NR; P=0.370; [underlined: Weight], kg, General linear model Change per longitudinal juice intake: Β=NR; P=0.494; [underlined: BMI], kg/m2, General linear model Change per longitudinal juice intake: Β=-0.057; P=0.099 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline; - Other: Parent height or BMI; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity, diet quality; - Not all key confounders accounted for; No information on baseline sample; no information on how missing data was handled (though amount of missing data was small); No preregistered data analysis plan; Funding:; Gerber Products Company; Tennessee Agricultural Experiment Station
Striegel-Moore, 2006^24^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,371; Participant characteristics at baseline: Female adolescents; - Age: Mean ~10y; - Female: 100%; - Race/ethnicity: Black 51%, White 49%; - SEP: SEP: <$10K: 17%; $10<20K: 14%; $20<30K: 15%; $30<40K: 14%; $40<50K: 12%; $50<75K: 17%; ≥$75K: 6%; - Anthropometry: Weight: ~ 37kg; Height: ~141 cm; - Physical activity: NR; - Smoking: NR; - Diet quality: Soda intake, g/d, Mean (SE): White, 135.45 (8.29); Black, 134.53 (7.85); - TEI: NR; Study beverage intake at baseline: Mean (SE): White: 110.46 (4.94) g/d; Black: 108.36 (4.86) g/d; Inclusion criteria: girls age 9 or 10 at study entry who identified themselves as “black” or “white”, non-Hispanic, with racially concordant parents or guardians | Exposure: 100% fruit juice intake (fruit or vegetable juice bottled, canned, fresh, frozen, sweetened or unsweetened; fruit nectars); Other exposures: Milk, SSB, LNCSB, Coffee/tea; Comparator: Fruit juice intake (continuous; 100 g/d); Exposure Assessment Methods and Timing: Validated 3-d food records; represents usual intake over 3 consecutive days (2 weekdays and 1 weekend day); At baseline, and annually for years 1-5, then at years 7, 8, 10; Outcome Assessment Methods and Timing: Weight measured twice by research staff using electronic scale. Height measured twice by research staff using stadiometer. BMI calculated as weight in kilograms divided by height in meters squared; Baseline, annually until 10y follow-up | [underlined: BMI], Linear regression; Change per 100g/d increase: B: 0.005, SE: 0.007, P>0.05 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, diet quality (other beverages, including SSB); - Other: Study site; Limitations:; - Did not account for key confounders: SEP, anthropometry at baseline, physical activity; - No information on non-completers; No preregistered data analysis plan; Funding:; NHLBI
Vandyousefi, 2021^4^; Prospective Cohort Study, SWIFT, United States; Analytic N = 835; Participant Characteristics; - Race/ethnicity: Non-Hispanic Asian: 37%, Hispanic: 30%, Non-Hispanic White: 23%, Non-Hispanic Black: 8%, Mixed race/other: 2%; - Maternal education: 14.9 (2.9) y; - Other SEP measure(s): Private insurance: 100%; - Maternal age: 33.4 (4.8) y; - Milk feeding practices: Any BF duration: 9 (7.2) mo; BF duration <6 mo: 40%, ≥6 mo: 60%; BF intensity at 6-9 wk: Exclusively BF: 22%, Mostly BF: 41%, Mixed/inconsistent FF: 21%, Exclusively or mostly FF: 16%; BF intensity and duration at 12 mo: <6: 53%, ≥6: 47%; - Child sex (female): 48%; - Birth weight: 3,397 (499) g; Birth length: 50.5 (2.4) cm; Size-at-birth percentile: LGA: 21%, AGA: 77%, SGA: 2%; - Gestational age: 39 (1.2) wk; - Other relevant characteristics: WIC recipient: 25%; GDM: 100%; Pre-pregnancy BMI: child normal weight: 28.5 (6.8), child with overweight: 31.7 (8.3), child with obesity: 33.6 (7.1), p<0.001; Exclusion criteria: missing data; mothers who had overt diabetes at study baseline | Exposure: 100% fruit juice; Comparator: fruit juice (categorical; Any vs none at birth to 1 y); [underlined: Exposure assessment method and timing]:; - Maternal surveys of date of introduction of fruit juice, sweetened beverages, water, sugar water, and other beverages, including types and amounts of each item; - 6-9 wk, 1 y post baseline (in-person surveys); Monthly from delivery to 1 y (mailed surveys); Study beverage intake:; - No SSB/no 100% fruit juice from birth to 1 y: 33%; - Any 100% fruit juice from birth to 1 y: 51%; Outcomes and assessment methods:; - At 2-5 y; - Weight and length from Electronic Health Records during well check visits. Age- and sex-standardized BMI percentiles calculated based on CDC growth percentiles. Overweight defined as BMI-for-age 85th-<95th percentile. Obesity defined as BMI-for-age ≥95th percentile. | [underlined: Overweight at 2-5 y], Logistic regression, OR (95% CI); [underlined: All participants]:; 100% fruit juice vs No SSB/no 100% fruit juice (ref): 1.24 (0.78, 1.98), p=0.48; [underlined: Adequate BF]:; 100% fruit juice vs No SSB/no 100% fruit juice (ref): 1.23 (0.73, 2.34), p=0.65; [underlined: Adequate EBF]:; 100% fruit juice vs No SSB/no 100% fruit juice (ref): 1.28 (0.73, 2.27), p=0.39; [underlined: Obesity at 2-5 y], Logistic regression, OR (95% CI); [underlined: All participants]:; 100% fruit juice vs No SSB/no 100% fruit juice (ref): 2.18 (1.17, 4.06), p=0.02; [underlined: Adequate BF]:; 100% fruit juice vs No SSB/no 100% fruit juice (ref): 3.13 (1.11, 7.29), p=0.03; [underlined: Adequate EBF]:; 100% fruit juice vs No SSB/no 100% fruit juice (ref): 4.17 (1.55, 11.17), p<0.01 | TEI adjusted: No; Confounders accounted for:; - SEP, sex, race/ethnicity, milk feeding practices; Confounders NOT accounted for:; - gestational age, baseline anthropometry; Additional model adjustments: Maternal education level, race/ethnicity, gestational weight gain, prenatal 3h 100g OGTT sum of 4 z-scores, GDM treatment type, gestational age at GDM diagnosis, WIC participation, parity, infant sex, infant size for gestational age, sex at birth, and age at BMI measurement; Limitations:; - Not all key confounders accounted for; - Limited to mothers with; GDM; - High attrition (19%); excluded sample having less education, more receiving WIC, and shorter BF duration; Funding sources:; NIDDK; NICHD; ADA
Vanselow, 2009^25^; PCS, Project EAT, U.S.; Analytic N=2,294; Participant characteristics at baseline: Adolescents; - Age: 14.9y; - Female: 55%; - Race/ethnicity: 62.9% white, 17.9% Asian American, 9.7% African American, 3.9% Hispanic, 2.7% American Indian, 2.9% mixed/other; - SEP: Parent education level (highest of the 2 parents), ~18%; - Anthropometry: NR; - Physical activity: Strenuous exercise, hr/wk, mean (SE), chi-square test Apple juice:; 0 svg/wk: 3.7 (0.1); 0.5-6 svg/wk: 3.9 (0.0); ≥7 svg/wk: 4.1 (0.1); P<0.05; Orange juice:; 0 sg/wk: 3.7 (0.1); 0.5-6 svg/wk: 3.8 (0.0); ≥7 svg/wk: 4.2 (0.1); P<0.05; - Smoking: NR; - Diet quality: Saturated fat, ~10.4% kcal; Fiber, g/1000 kcal, mean (SE), chi-square test; Apple juice: 0 svg/wk: 7.5 (0.1); 0.5-6; svg/wk: 7.9 (0.1); ≥7 svg/wk: 8.4 (0.1); P<0.05; Orange juice: 0 svg/wk: 7.2 (0.2); 0.5-6; svg/wk: 7.8 (0.1); ≥7 svg/wk: 8.6 (0.1); P<0.05; Calcium: ~565 mg/d; - TEI: Kcal/d, mean (SE), chi-square test; Apple juice:; 0 svg/wk: 1652 (55); 0.5-6 svg/wk: 1984 (25); ≥7 svg/wk: 2661 (40); P<0.05; Orange juice:; 0 svg/wk: 1721 (62); 0.5-6 svg/wk: 1920 (25); ≥7 svg/wk: 2633 (37); P<0.05; Study beverage intake at baseline: Apple juice: 13.3% 0 svg/wk, 62.8% 0.5-6 svg/wk, 23.9% ≥7 svg/wk; Orange juice: 10.4% 0 svg/wk, 61.4% 0.5-6 svg/wk, 28.2% ≥7 svg/wk; Exclusion criteria: lost to follow-up, missing data, implausible energy intakes | Exposure: Apple and orange juice. Serving size NR.; Other exposures: SSB, LNCSB, dairy milk; Comparator: Different intake of juice, categorical intake (0, 0.5-6, ≥7 svg/wk); Exposure Assessment Methods and Timing: Validated 149-item youth and adolescent food-frequency questionnaire (YAQ). Responses ranged from “never/less than once per month” to ≥4 glasses, cups, cans, or drinks per day depending on beverage type.; Baseline, 5y; Outcome Assessment Methods and Timing: BMI calculated from self-reported height and weight. Overweight considered as BMI ≥85th percentile for sex and age; Baseline, 5y | [underlined: Change in BMI over 5y by number of servings/wk of time 2 juice intake], kg/m2, mean (SE), multivariable linear regression; Apple juice; Model 1; 0 svg/wk: 1.89 (0.16); 0.5-6 svg/wk: 1.89 (0.09); ≥7 svg/wk: 1.56 (0.20); P=0.30; Model 2; 0 svg/wk: 1.84 (0.17); 0.5-6 svg/wk: 1.91 (0.09); ≥7 svg/wk: 1.60 (0.21); P=0.42; Orange juice; Model 1; 0 svg/wk: 1.83 (0.19); 0.5-6 svg/wk: 1.90 (0.09); ≥7 svg/wk: 1.54 (0.18); P=0.20; Model 2; 0 svg/wk: 1.84 (0.17); 0.5-6 svg/wk: 1.91 (0.09); ≥7 svg/wk: 1.60 (0.21); P=0.42 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity (models 2 and 3), diet quality (models 2 and 3, SSB intake); - Other: Model 1: key confounders as listed; baseline beverage consumption of the beverage being analyzed Model 2: all beverages assessed together in the model; adjusted for key confounders and all baseline beverages, cohort, change in BMI, baseline and time 2 strenuous physical activity, and time 2 weekday television watching and coffee and tea consumption; Limitations:; - Did not account for key confounders:; - No preregistered data analysis plan; No information on non-completers; Lack of accurate assessment of exposure portion sizes; Funding:; HHS (Maternal and Child Health Bureau, Health Resources and Services Administration)
Wan, 2020^26^; PCS, Framingham Children’s Study, U.S.; Analytic N=100; Participant characteristics at baseline: preschool-aged children; - Age: Mean ~5y; - Female: 39%; - Race/ethnicity: “largely of middle-class Caucasian ancestry”; - SEP: Mother’s education, % college; <0.5 cups/d: 20%; 0.5 − < 1 cup/d: 40%; ≥1 cup/d: 50%; p-trend=0.0116; - Anthropometry: BMI, Mean ~16.3 kg/m2; - Physical activity: Activity ~11 Caltrac counts/hr; - Smoking: NR; - Diet quality: HEI 2015 Score, mean (SD); <0.5 cups/d: 48 (2); 0.5 − < 1 cup/d: 52.4 (6.1); ≥1 cup/d: 55.0 (6.7); p-trend=0.0002; p-trend=0.0116; - TEI: ~1600 kcal/d; Study beverage intake at baseline: 100% juice intake: 35% <0.5 cup/d; 35% 0.5-1 cup/d, 30% ≥1 cup/d; Inclusion criteria: participants with dietary data at baseline and throughout follow-up | Exposure: 100% fruit juice and 100% juice blends (blended with other 100% juices), such as apple juice, orange juice, and cranberry juice blends; excluded part-juice beverages and tomato juice. Measured in USDA-defined cup-equivalents per day; Other exposures: none; Comparator: Categorical (<0.5 cups/d, 0.5-<1.0 cups/d, ≥1 cups/d); Exposure Assessment Methods and Timing: Multiple sets of 3d diet records; completed by parents prior to age 10y; At baseline, then annually for 10y. Only baseline (3-6y) measurement used in analysis; Outcome Assessment Methods and Timing: Height and weight measured at annual clinic exam; used to calculate BMI At baseline, then annually for 10y | [underlined: Change in BMI (kg/m2) from 3-17y based on juice intake at 3-6y]; NS, data NR (figure only) | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity; - Other: maternal BMI, TV and video viewing time; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - Exposure data only measured at baseline; No preregistered data analysis plan; Funding:; NHLBI; Juice Products Association
Welsh, 2005^27^; PCS, Missouri WIC Program, U.S.; Analytic N=10,904; Participant characteristics at baseline: Children; - Age: Mean: ~34 mo; - Female: 50%; - Race/ethnicity: White: 88.6%; Black: 5.8%; Other: 5.6%; - SEP: All enrolled in Missouri WIC program; - Anthropometry: BMI %: Normal or underweight 75.5%, At risk for overweight 14.5%, Overweight 10.1%; - Physical activity: NR; - Smoking: NR; - Diet quality: Mean sweet drinks/d: 2.9; - TEI: Mean: 1780 kcal/d; Study beverage intake at baseline: Vitamin C juice at baseline (drinks/d): 0-<1, 61.0%; 1-<2, 17.6%; 2-<3, 17.7%; ≥3, 3.7%; Mean=1.0 drinks/d; Other juice at baseline (drinks/d): 0-<1, 61.9%; 1-<2, 16.8%; 2-<3, 17.7%; ≥3, 3.6%; Other juice: Mean=1.0 drinks/d; Inclusion criteria: children aged 2-3y at baseline who were enrolled in Missouri WIC Program between January 1999 and December 2001; at least one clinic visit where height and weight data were collected and reported to PedNSS and one follow-up clinic visit with height and weight data collected 1y later; Excluded: missing values for key dietary or outcome variables, extreme BMI values (z score < −4 or >5); extremes in total energy intake (<800 or >3500 kcal) | Exposure: Fruit juice intake (includes vitamin C-containing juices (natural or added), and other juices). 1 drink=1 parent-defined serving; Other exposures: SSB; Comparator: Fruit juice intake (categorical; drinks/d): 0-<1 (ref); 1-<2; 2-<3; ≥3; Exposure Assessment Methods and Timing: Validated FFQ completed by parents; represents usual intake in the last 4wk; Baseline; Outcome Assessment Methods and Timing: Standing height measured using standard measuring board. Weight measured using pediatric scale or beam balance scale. Age- and sex-specific BMI percentile based on 2000 CDC growth chart. Normal or underweight (BMI<85th%), at risk for overweight (BMI 85th-<95th percentile), overweight (BMI≥95th percentile); Baseline, 1y follow-up | [underlined: Overweight at follow up (BMI >95th%),] by fruit juice intake (drinks/d) stratified by baseline weight status: Logistic regression, OR (95% CI) Normal or underweight at baseline; 0-<1 (n=2768, Ref); 1-<2 (n=1815): 1.1 (0.8, 1.5); 2-<3 (n=2210): 1.0 (0.7, 1.4); ≥3 (n=1435): 1.2 (0.8, 1.7); At risk of overweight at baseline; 0-<1 (n=573, Ref); 1-<2 (n=345): 1.1 (0.8, 1.6); 2-<3 (n=405): 1.0 (0.7, 1.4); ≥3 (n=256): 0.8 (0.5, 1.1); Overweight at baseline; 0-<1 (n=390), Ref; 1-<2 (n=259): 1.5 (1.0, 2.1); 2-<3 (n=262): 1.5 (1.1, 2.2); ≥3 (n=186): 1.2 (0.8, 1.8) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, diet quality (sweet food intake, highfat food intake); - Other:; Limitations:; - Did not account for key confounders: physical activity; - Not all key confounders accounted for; Exposure data only measured at baseline; Attrition rate unclear, but may be >70%; No preregistered data analysis plan; Funding:; NR
Zheng, 2015(a)^28^; PCS, Childhood Asthma Prevention Study (RCT), Australia; Analytic N=158; Participant characteristics at baseline: Children; - Age: Mean: ~8y; - Female: 48%; - Race/ethnicity: Mother born in Australia/New Zealand ~78%; Father born in Australia/New Zealand ~73%; - SEP: Maternal education level >12y; ~55%; Paternal education level >12y; ~58%; Living in disadvantaged area; ~20%; - Anthropometry: BMI z-score, Mean (SD): 0.4(1.0); Overweight/obesity: 27.2%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Mean ~8.0 MJ/d (~1,912 kcal/d); Study beverage intake at baseline: Fruit juice intake at baseline (g/d), Mean (SD): ~90(89); Inclusion criteria: participants in CAPS RCT; participation in anthropometric assessment at 8y and dietary assessment at age 9y; Excluded: incomplete diet data, misreporting of energy intake, missing anthropometric data | Exposure: 100% fruit juice intake (apple, blackcurrant, grape, orange, and fruit blend); Other exposures: Milk, SSB, LNCSB; Comparator: Fruit juice intake (100 g/d) modeled continuously; Exposure Assessment Methods and Timing: Three 24-hr dietary recalls via phone using multiple pass approach completed by children with parental assistance; Represents usual dietary intake on non-consecutive weekdays and weekends; At 1y follow-up (age 9y); Outcome Assessment Methods and Timing: Weight measured to nearest 0.1kg. Height measured using stadiometer. Age- and sex-specific BMI z-scores calculated using 2000 CDC growth charts. Percentage body fat (%BF) measured by bioimpedance analysis.; Baseline (age 8y), and 3.5y follow-up (age 11.5y) | [underlined: BMI z-score], Linear regression; Change per 100 g/d increase, β (SE):; TEI unadjusted: 0.07 (0.05), P=0.15; TEI adjusted: 0.07 (0.05), P=0.12; [underlined: %Body Fat], Linear regression; Change per 100 g/d increase, β (SE):; TEI unadjusted: −0.10 (0.45), P=0.84; TEI adjusted: −0.05 (0.44), P=0.91 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP (socioeconomic index for area score, parental education level), anthropometry at baseline (BMI z-score); - Other: Maternal age at birth, presence of gestational diabetes, exclusive breastfeeding at 3mo, pubertal status, randomization group (omega-3 fatty acid dietary supplementation and house dust mite reduction); Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity, diet quality; - Not all key confounders accounted for; Exposure measured at baseline only; Baseline data for exposure and outcome occurred 1 year apart; Funding:; National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead
Zheng, 2015(c)^29^; PCS, European Youth Heart Study (EYHS), Denmark; Analytic N=358; Participant characteristics at baseline: Children; - Age: Mean (SD): 9.6y (0.4); - Female: 56%; - Race/ethnicity: NR; - SEP: Maternal education: 47% Low (elementary, high school, or vocational education); - Anthropometry: BMI 17.2 (2.3) kg/m2; BMI z-score 0.4 (1.1); - Physical activity: 55% Active (regular exercise); - Smoking: NR; - Diet quality: SSB, g/d, Mean (SD): 154 (205); - TEI: Mean: 9.1 (2.3) MJ/d; Study beverage intake at baseline:; Fruit juice intake, mean (SD): 62.4 (139.0) g/d; Inclusion criteria: third-grade children who participated in the Danish part of EYHS in 1997 with 6-y follow-up in 2003; Excluded: incomplete diet or anthropometric data; underreporting energy intake | Exposure: 100% pure fruit juice intake (apple, orange, or other juice); Other exposures: Milk, SSB, Coffee/tea; Comparator: Fruit juice intake (100g/d) modeled continuously; Exposure Assessment Methods and Timing: One 24h recall face-to-face interview supplemented with parent-assisted food record; represents food intake; Baseline (age 9); Outcome Assessment Methods and Timing: Height measured bare feet to nearest 5mm using stadiometer. Weight measured to nearest 0.1 kg using beam balance scale. BMI calculated as kg/m2. Age- and sex-specific BMI z-score generated using the least mean squares method. Waist circumference (WC) measured twice with metal anthropometric tape (mean was used). Sum of 4 skinfolds (Σ4SF) obtained by adding average skinfolds of 4 sites (biceps, triceps, subscapular, and suprailiac) that were measured in duplicate with Harpenden fat calipers; Baseline, 6y follow up | Base Model (Model 1 in paper) adjusted for confounders listed to the left, but did not adjust for TEI; Standard Multivariate Model (Model 2 in paper) adjusted for TEI; Energy Partition Model (Model 3 in paper) included energy-containing beverages only (ie, excluded water) and adjusted for energy from non-beverage sources.; [underlined: Change in WC age 9-15y]: cm, Per 100 g/d increase, Linear regression, β (SE); Base Model: −0.01 (0.22), P=0.59; TEI Model: −0.01 (0.23), P=0.96; Energy Partition: −0.01 (0.22), P=0.95; [underlined: Change in Σ4SF age 9-15y]: mm, Per 100 g/d increase, Linear regression, β (SE); Base Model: 0.47 (0.54), P=0.38; TEI Model: 0.58 (0.57), P=0.31; Energy Partition: 0.60 (0.56), P=0.28; Base Model (Model 1 in paper) adjusted for confounders listed to the left, but did not adjust for TEI; Standard Multivariate Model (Model 2 in paper) adjusted for TEI; Energy Partition Model (Model 3 in paper) included energy-containing beverages only (ie, excluded water) and adjusted for energy from non-beverage sources.; [underlined: Change in BMI z-score age 9-15y:] Per 100 g/d increase, Linear regression, β (SE); Base Model: 0.02 (0.03), P=0.39; +AR2TEI Model: 0.03 (0.03), P=0.34; Energy Partition: 0.03 (0.03), P=0.35 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP (maternal education), anthropometry at baseline (BMI z-score or WC), physical activity, diet quality (other beverages); - Other: Pubertal status, Sex x SEP, energy from non-beverage sources; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Not all key confounders accounted for; Exposure measured at baseline only; No preregistered data analysis plan; Funding:; NR

a Abbreviations: AGA: appropriate for gestational age; β: beta coefficient; BF: breast-fed; BM: birth mother; BMI: body mass index; BMI-SDS: BMI standard deviation score; BMIZ: BMI z-score; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; d: day; DEXA/DXA: dual energy x-ray absorptiometry; DQIS: diet quality index score; EER: estimated energy requirement; EI: energy intake; FF: formula-fed; FFQ: food frequency questionnaire; fl oz: fluid ounces; FMI: fat mass index; g: grams; GDM: gestational diabetes mellitus; HAZ: height-for-age z-score; HHS: Department of Health and Human Services; kg: kilogram; kJ: kilojoules; LGA: large for gestational age; LNCSB: low- and no-calorie sweetened beverages; M: meter; mL: milliliter; MJ: megajoule; mo: month; MZ: monozygotic; NHLBI: National Heart, Lung, and Blood Institute; NHS II: Nurses Health Study II; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NR: not reported; NS: not significant; OGTT: oral glucose tolerance test; OR: odds ratio; Oz: ounce; PCS: prospective cohort study; RCT: randomized controlled trial; Ref: reference; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SGA: small for gestational age; SSB: sugar sweetened beverages; Svg: serving; TEI: total energy intake; USDA: United States Department of Agriculture; WAZ: weight-for-age z-score; WC: waist circumference; WIC: Special Supplemental Nutrition Program for Women, Infants & Children; Wk: week; WLZ: weight-for-length z-score; Wt: weight; y: year(s)

Table 12 Risk of bias for randomized controlled trials examining 100% juice consumption in infancy through adolescence and growth, body composition, and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Lambourne, 2013^13^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 13 Risk of bias for observational studies examining 100% juice consumption in infancy through adolescence and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Amaro-Rivera, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Berkey, 2004^5^ | HIGH | LOW | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Blum, 2005^6^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Carlson, 2012^7^ | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Dong, 2015^8^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dubois, 2016^9^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Field, 2003^10^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Fiorito, 2009^11^ | HIGH | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
Gaffney, 2012^2^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Guerrero, 2016^12^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Johnson, 2007^14^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kral, 2008^15^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Libuda, 2008^16^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Mahoney, 2018^3^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Marshall, 2019^17^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Mrdjenovic, 2003^18^ | HIGH | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Newby, 2004^19^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Sakaki, 2021a^21^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Sakaki, 2021b^20^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Shefferly, 2016^22^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Skinner, 2001^23^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Striegel-Moore, 2006^24^ | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Vandyousefi, 2021^4^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Vanselow, 2009^25^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Wan, 2020^26^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Welsh, 2005^27^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zheng, 2015a^28^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zheng, 2015c^29^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )

Table 14 Evidence examining the relationship between 100% juice consumption in adults and body composition and risk of obesity^a^

Study and Population Characteristics | Intervention, Comparator, and Outcome | Results | Confounding and Study Limitations
Randomized Controlled Trials
Aptekmann, 2010^30^; RCT-Parallel, Brazil; Baseline N=30, Analytic N=26 (Attrition: 13%); Power: NR; Participant characteristics at baseline: Children and adolescents, adults, older adults, individuals during pregnancy and postpartum (can also specific men/women, girls/boys, etc as applicable); - Age: 30–48y; - Female: 100%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Overweight: 37%, Obesity: 63%;; Mean weight: 75.5 (14.2) kg; - Physical activity: all “sedentary”, lack of regular physical activity was inclusion criterion; - Smoking: NR; - Diet quality: NR; - TEI: ~8 MJ; Study beverage intake at baseline: irregular or no consumption of orange juice (inclusion criteria); Inclusion criteria: LDL-C < 160 mg/dL and triglycerides < 200 mg/dL; irregular or no consumption of orange juice and lack of regular physical activity; absence of thyroid and/or kidney disorders and diabetes; not taking hormone replacement therapy or vitamin or mineral supplements; not taking cholesterol-lowering medication; compliance with aerobic training program (≤1 absence in 12 sessions/mo (1 mo) and ≤3 sessions out of 36 sessions (3mo)) | Intervention: Consume 500 mL/d of orange juice + 1hr aerobic training 3 times/wk, no other dietary guidance given, n=13; Study purpose: to investigate how consumption of orange juice associated with aerobic training affected serum lipids and physical characteristics of overweight, middle-aged women; Other interventions: 1h aerobic training sessions 3d/wk; Comparator: Usual intake (little/no orange juice); plus 1h aerobic training sessions 3d/wk, n=13; Duration: 3mo; Compliance: verified indirectly by self-report; all confirmed they drank the preset amount of orange juice daily; Outcomes and assessment methods:; Weight and height measured, BMI calculated. Body fat (%): assessed early in the morning with a bioelectrical impedance device before the participants broke the overnight fast or exercised. Skinfold thickness: Triceps, abdominal and thigh skinfold thicknesses were measured three times with a Lange Skinfold Caliper (Cambridge Scientific Industries, Inc.), average was used as the reference value; 1st and 90th day | Body fat (%), Paired t-test, Mean (SD); Within group, over time: before, after; Control: 39.3 (7.33), 33.8 (7.98), P<0.05; OJ: 37.7 (7.56), 33.4 (7.42), P<0.05; Between groups, at follow-up: NS; Skinfold thickness, mm, Mean (SD) Tricep; Within group, over time: before, after; Control: 32.0 (10.1), 27.3 (9.33), P<0.05; OJ: 31.9 (7.90), 26.6 (6.85), P<0.05; Between groups, at follow-up: NS; Abdominal; Within group, over time: before, after; Control: 30.2 (14.3), 25.5 (11.9), P<0.05; OJ: 32.2 (11.8), 29.3 (9.60), P<0.05; Between groups, at follow-up: NS; Thigh; Within group, over time: before, after; Control: 53.0 (12.8), 45.9 (14.9), P<0.05; OJ: 52.6 (11.5), 43.4 (9.99), P<0.05; Between groups, at follow-up: NS; Weight, kg, Paired t-test, Mean (SD); Within group, over time: before, after; Control: 76.3 (15.3), 74.5 (15.9), P<0.05; OJ: 74.6 (13.0), 73.6 (12.4), P<0.05; Between groups, at follow-up: NS; BMI, kg/m2, Paired t-test, Mean (SD); Within group, over time: before, after; Control: 29.0 (5.53), 28.3 (5.81), P<0.05; OJ: 28.4 (4.46), 28.1 (4.47), P<0.05; Between groups, at follow-up: NS | Model adjustments:; - TEI: yes and no; - Other: Nutrient intake; (carbohydrate, total fat, SFA, PUFA, MUFA, Vitamin C, folate) and cholesterol (all NS); Limitations:; - Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; Fischer Group; “Associacão Laranja Brasil”
Hollis, 2009^40^; RCT-Parallel, U.S.; Baseline N=86, Analytic N=76 (Attrition: 12%); Power: NR; Participant characteristics at baseline: adults with overweight; - Age: 18–50y, Mean ~25y (P<0.05, between groups); - Female: NR (men & women were included); - Race/ethnicity: NR; - SES: NR; - Anthropometry: BMI ~27, NS between groups; - Physical activity: NR; - Smoking: 100% nonsmokers (inclusion criteria: no use of tobacco products); - Diet quality: NR; - TEI: ~8860 kJ; Study beverage intake at baseline: Intake of CGJ or red wine ≤2 times/wk (inclusion criteria); Inclusion criteria: general good health; age 18 to 50 years; BMI 25.0–29.9 (kg/m2); customary consumption of grape juice or red wine no more than twice per week; no use of dietary supplements that would confound analysis of antioxidant capacity; no use of tobacco products; no use of medication that would confound the study outcome measures. | Intervention: Consume 480 mL/d of Concord grape juice, no other dietary guidance given, n=25; Study purpose: to assess the effects of Concord grape juice consumption for 12 wk on appetite, diet, body weight, lipid profile, and antioxidant status; Other interventions: polyphenol-free substitute grape-flavored drink, n=26; Comparator: Control, no treatment (usual intake of CGJ or red wine ≤2 times/wk), n=25; Duration: 12wk; Compliance: NR; Outcomes and assessment methods:; Weight measured on calibrated scales. Body composition was measured using bioelectrical-impedance analysis. Waist circumference measured using a flexible tape to the nearest millimeter; At weeks: 0, 2, 4, 6, 8, 10, 12 | Waist circumference, cm, Mean (SD); Within group: Baseline, 12wk; Control: 33.4 (2.5), 33.1 (3.0), P=NS; CGJ: 32.8 (2.6), 32.3 (2.8), P<0.005; Between groups: P=NS; Weight, kg, Mean (SD); Within group: Baseline, 12wk; Control: 77.6 (10.3), 77.7 (9.8), P=NS; CGJ: 79.0 (8.4), 79.7 (9.5) P=NS; Between groups: P=NS; BMI, kg/m2, Mean (SD); Within group: Baseline, 12wk; Control: 27.3 (1.5), 27.1 (2.0), P=NS; CGJ: 27.0 (1.6), 27.1 (2.0), P=NS; Between groups: P=NS | Model adjustments:; - TEI: no; - Other:; Limitations:; - Baseline difference in age, sex NR; Methods for randomization and concealment NR; No power calculation; No measure of compliance; No preregistered data analysis plan; Funding:; Welch Foods Inc.
Shenoy, 2010^48^; RCT-Parallel, U.S.; Baseline N=81, Analytic N=60 (Attrition: 25%); Power: NR; Participant characteristics at baseline: adults with metabolic syndrome (35–65); - Age: mean (SD) 49.8 (6.9); - Female: 73%; - Race and/or ethnicity: White: 16.5%; Black: 57%; Mexican-American: 22.8%; Other: 3.7%; - SEP: High school education or less: 58.9%; - Anthropometry: Mean (SD); wt 105.6 kg (18.4); BMI 37.8 (4.9); WC 115.8 cm (13.3); - Physical activity: NR; - Smoking: Current smoker: 13.3%; - Alcohol intake: NR; - TEI: Mean (SD); Control: 1898.5 (599.9); 8oz group: 2015.9 (931.9); 16oz group: 2184 (703.6); Study beverage intake at baseline: 8oz juice group: 100% adherence 16 oz juice group: 56% adherence; Inclusion criteria: metabolic syndrome defined by the NCEP Adult Treatment Panel: met 3 out 5 criteria 1) WC for men > 40 in, for women > 35 in; 2) triglycerides > 150 mg/dL; 3) systolic BP > 130 mmHg or diastolic BP > 85 mmHg; 4) fasting blood glucose > 100 mg/dL; 5) HDL-C < 40 mg/dl for men and < 50 mg/dl for females; Body 30- 50 kg/m^2^, 16–35 years of age Excluded: use of anxiolytics or antidepressive medication, hormone replacement therapy, alcohol in excess of 1 ounce/d, diabetes controlled with insulin, hyper- or hypothyroidism, inflammatory disorders, treatment with corticosteroids and anti-inflammatory drugs, routine use of aspirin and other NSAIDs, or hx of a major cardiovascular; abnormal CBC defined as low/high WBCs (less than 4.0 K/mm3 or greater than 11 K/mm3); hemoglobin (less than 11.5 or greater than 17g/dL), platelets (less than 130 K/mm3 or greater than 450 K/mm3); or a Beck Depression Inventory® scale score of 21 or above | Intervention: V8®; Campbell Soup Company, Camden, NJ) provided 50 calories, 140 mg sodium; Other interventions: Education on DASH diet, caloric diet prescription (1600 for women, and 1800 for men); Comparator: No juice, 8 oz/d of vegetablejuice, 16 oz/d vegetable juice; Duration: 12 weeks; Compliance: Daily consumption reported on checklist; adherence was considered as 85% to beverage allotment; Outcomes and assessment methods:; Height measured on stadiometer, weight measured on electronic scale, Body mass index (kg) calculated as weight (kg) divided by height squared (m2); 6 and 12 wk | No statistically significant differences in weight loss over time between groups.; Weight change baseline to 12-wk follow up: aggregated juice groups compared to control; adjusted model (gender, education, and age); data not shown; Completers: F= 4.3, P=0.02; LOCF and ITT: F3.8, P=0.03 | Model adjustments:; - TEI: yes and no; - Other: aggregated data model adjusted for age, sex, and education; Limitations:; - Methods for concealment NR; Differences in attrition; Unclear if outcome assessors were aware of intervention assignment; No power calculation; High attrition; No preregistered data analysis plan; Funding:; Campbell Soup Company
Silver, 2011^49^; RCT-Parallel, U.S.; Baseline N=95, Analytic N=68 (Attrition: 28%); Power: nQuery Advisor with 85% power to detect a minimum difference in total weight loss of 3.3 kg between groups, assuming a common SD of 3 kg and a 15–20% drop out rate, 23 subjects per group needed; Participant characteristics at baseline: adults (21–50y); - Age: mean age 38.7 ± 8.2y; - Female: 75%; - Race/ethnicity: White: 60%; Black: 40%; - SEP: High school: 10%; Undergraduate: 62%; Graduate: 27%; - Anthropometry: mean BMI was 35.6 ± 3.3 kg/m2; - Physical activity: NR; - Smoking: Previous smoker: 11.7%; - Alcohol intake: NR; - TEI: 12.5% calorie restriction from baseline intake; mean intake not reported; Study beverage intake at baseline: 127g 20 minutes before meals; Inclusion criteria: BMI 30–39.9 kg/m2; weight under 300 lb; Excluded: diabetes, cardiovascular, liver or kidney disease; medications for estrogen replacement, thyroid disease, depression, gastrointestinal disorders; medications metabolized by the cytochrome P450 3A4 enzyme; orexigenic agents; and food allergies or medically restricted diets, weight change >5 pounds within 3 mo, bariatric surgery, disordered eating, non-restrained eating, “yes” to PAR-Q questions, serum triglyceride or LDL-cholesterol level >200 mg/dL, abnormal liver enzyme level, tobacco use, illicit drug use, alcohol intake >1 drink/d, pregnancy (by serum beta-HCG level) or lactation | Intervention: V8®; Campbell Soup Company, Camden, NJ) provided 50 calories, 140 mg sodium; Other interventions: Education on DASH diet, caloric diet prescription (1600 for women, and 1800 for men); Comparator: No juice, 8 oz/d of vegetable juice, 16 oz/d vegetable juice; Duration: 12 weeks; Compliance: Daily consumption reported on checklist; adherence was considered as 85% to beverage allotment; Outcomes and assessment methods:; Height measured on stadiometer, weight measured on electronic scale, Body mass index (kg) calculated as weight (kg) divided by height squared (m2); 6 and 12 wk | BMI change from baseline: controlled for baseline weight, p-value difference between group; - 1.9 ± 1.4, p=0.523; WC (cm) change from baseline: controlled for baseline WC, p-value difference between group; - 5.5 ± 5.7, p=0.189; Total body fat %: controlled for baseline body fat, p-value difference between group; - 1.1 ± 1.9, p=0.489 | Model adjustments:; - TEI: yes and no; - Other: baseline anthropometric measures; Limitations:; - Methods for concealment NR; Concerns with deviations from intended intervention (intent to treat); Unclear if outcome assessors were aware of intervention assignment; Funding:; State of Florida, Department of Citrus, National Center for Research Resources, NIH, Tennessee Valley Healthcare System, Vanderbilt Diabetes Research and Training Center
Prospective cohort studies
Auerbach, 2018^31^; PCS, Women’s Health Initiative, U.S.; Analytic N=49,106; Participant characteristics at baseline: Postmenopausal women; - Age: Mean (SD): 57.9 (4.1) y; - Female: 100%; - Race/ethnicity: White: 84%; Black (“African American”): 7.6%; Asian(“/Pacific”): 3.0%; Hispanic (“/Latino”): 4.0%; - SEP: College degree or higher 48%, Annual household income ≥ $75,000 15.4%; - Anthropometry: Mean (SD), BMI= 26.2 (4.0) kg/m2; - Physical activity: Recreational physical activity level (MET-hours/wk): 4.3 (3.9); - Smoking: Current smoking 7.1%; - Diet quality: HEI diet quality score, Mean (SD): 67.9 (10.5); - TEI: Mean (SD): 1636 (620) kcal/d; Study beverage intake at baseline: Mean (SD): 0.67 (0.63) svg/d; Inclusion criteria: female; postmenopausal; age 50–79y; Excluded: missing baseline weight, year 3 weight, baseline 100% fruit juice intake, year 3 100% fruit juice intake, baseline age >65y, BMI >35.0 kg/m2, implausible energy intake | Exposure: 100% fruit juice intake (1 svg = 6 oz); Other exposures: SSB; Comparator: 100% fruit juice intake (continuous; svg/d increase over 3y); Assessment methods and timing: Validated FFQ; represents usual intake; baseline, 3y; Outcomes and assessment methods:; Weight measured using standardized protocol and calibrated scales baseline, 3y follow-up | Weight, lb/3-year change per svg/d increase, Linear mixed effects model, B (95% CI):; TEI unadj: 0.39 (0.10, 0.69); TEI adj: 0.33 (0.04, 0.63); Analysis with Multiple Imputation (n=74,397); TEI unadj: 0.39 (0.15, 0.63); TEI adj: 0.33 (0.09, 0.58); Stratified by BMI group; BMI 18.5–24.9 (n=20,494):; TEI unadj: 0.42 (−0.07, 0.91); TEI adj: 0.38 (−0.11, 0.87); BMI 25.0–29.9 (n=18,543):; TEI unadj: 0.28 (−0.15, 0.71); TEI adj: 0.23 (−0.20, 0.66); BMI 30.0–34.9 (n=9,588):; TEI unadj: 0.59 (−0.07, 1.25); TEI adj: 0.50 (−0.15, 1.16); “Results did not differ in stratified analyses of 5-year increments of baseline age or baseline BMI category, and interaction terms for change in 100% fruit juice consumption and baseline age (P=.64) and baseline BMI (P=.66) were not significant” (Data NR) | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (total household income, education level), anthropometry at baseline (BMI), physical activity, diet quality (3-y change in HEI diet quality score), smoking; - Other: Hormone replacement therapy status; Limitations:; - Did not account for key confounders: anthropometry at baseline (weight); - No preregistered data analysis plan; Funding:; NHLBI; NIH
Bes-Rastrollo, 2008^32^; PCS, Nurses’ Health Study II, U.S.; Analytic N=50,026; Participant characteristics at baseline: Adult women; - Age: Mean (SD): 36.5y (4.6); - Female: 100%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean (SD): BMI: 24.2 (5.0); Weight, kg: 65.9 (14.3); - Physical activity: MET-h/wk, Mean (SD): 20.4 (26.4); - Smoking: Current: 11%; - Diet quality: Dietary energy density, kcal/g (food only): 1.2 (0.4); Dietary ED, kcal/g (food+beverages): 1.1 (0.3); Food group intake, Mean (SD):; Vegetables, g/d: 159 (99); Fruit, g/d: 176 (118); Other macronutrient and food group intakes reported in paper; - TEI: Mean (SD), kcal/d 1771 (522); Study beverage intake at baseline: NR; Excluded: missing dietary (completely missing or >9 missing items), physical activity, weight, or follow-up data; unreasonable energy intakes; history of diabetes or CVD; cancer; pregnancy | Exposure: Tomato juice, Orange juice, Apple juice; Other exposures: SSB, LNCSB, milk, coffee, tea; Comparator: Categorical intake (Highest vs. lowest tertile of change); Assessment methods and timing: Self-administered semi-quantitative FFQ; Represents intake during previous year Baseline, 8y; Outcomes and assessment methods:; Weight, self-reported through biennial questionnaires; Baseline, 8y | Weight change over 8y, kg, Linear regression Orange juice; Lowest tertile (ref) vs Highest tertile: Data NR, P<0.05; Apple juice; Lowest tertile (ref) vs Highest tertile: Data NR, P=NS; Tomato juice; Lowest tertile (ref) vs Highest tertile: Data NR, P=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, physical activity, smoking; - Other: Postmenopausal hormone use, oral contraceptive use, changes in confounders between time periods; Limitations:; - Did not account for key confounders: race/ethnicity, SEP, anthropometry at baseline, diet quality; - Not all key confounders accounted for; Exposures not well defined and FFQ varied over time; No info on non-completers; Self-reported weight; No preregistered data analysis plan; Funding:; NIH; Spanish Ministry of Education; Fundacion Caja Madrid; Amigos de la Universidad de Navarra; AHA Established Investigator Award
Castellana, 2020^33^; PCS, Multicenter Italian study on Cholelithiasis (MICOL) and GreatAGE, Italy; Analytic N=734; Participant characteristics at baseline: older adults; - Age: mean (SD): 65.95; - Female: 42%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean (SD): 29.83 (5.04); - Physical activity: NR; - Smoking: NR; - mean intake g/day:; leafy vegetables 63.14; Fruiting vegetables 93.24; Root vegetables 7.81; Other vegetables 74.65; Fruit 595.53; - TEI: mean (SD) 2182.76; Study beverage intake at baseline: NR; Inclusion criteria: without impaired health indicators at baseline, participated in both MICOL3 and greatAGE cohorts | Exposure: fruit juices; Other exposures: SSB, coffee; Comparator: Amount of intake (g/day); Assessment methods and timing: FFQ- 85 items reflected regional diet MICOL3 − 2005–2006; Outcomes and assessment methods:; Height and weight measurements were performed using a Seca 220 altimeter and a Seca 711 scale M3 2005–2006 and greatAGE 2012–2018 | BMI gain >1.5 kg/m2: p-values, linear regression with intake grams/day; p=0.673 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, smoking; - Other:; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity, diet quality,; - Exposure not well defined; Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; Italian Ministry of Health with “Ricerca Corrente 2019” Grant.
Chen, 2009^34^; PCS, Secondary analysis of PREMIER randomized trial, U.S.; Analytic N=810; Participant characteristics at baseline: adults enrolled in an 18mo behavioral intervention trial to lower BP; - Age: Mean (SD) = 50 (8.9) y, Range 25–79y; - Female: 62%; - Race/ethnicity: African American: 34.4%, Non-Hispanic White: 64.2%, All Others: 1.4%; - SEP: 57.2% college degree or above; 70% annual household income >$45,000, 65.2% married; - Anthropometry: BMI Mean (SD): 33.1 (5.8) kg/m2; 65.2% BMI ≥ 30, 29% BMI 25.0–29.9, 5.4% BMI < 25; - Physical activity: EER Mean (SD) 33.7 (2.9) kcal/kg·d; - Smoking: 4.8% current smokers; - Alcohol intake: Liquid calorie intake, Mean (SD): 356 (237) kcal/d; % of total energy intake from liquid calories, Mean (SD): 19 (11.5); - TEI: NR; Study beverage intake at baseline: 100% juice intake at baseline: Mean (SD), 139.0 (201.1) mL/d; (~4.7 (6.8) oz/d); Inclusion criteria: adults with prehypertension or stage 1 hypertension (systolic BP 120–159 mmHg and diastolic BP 80–95 mmHg).; Excluded: routine use of antihypertensive medications, weight loss medication, or oral steroids; those with diabetes, history of a cardiovascular event, CHF, current symptoms of angina or PVD, cancer diagnosis or treatment in past 2y (except for nonmelanoma skin cancer), renal insufficiency, or psychiatric hospitalization within the past 2y | Exposure: 100% fruit and vegetable juice; Other exposures: Milk, SSB, LNCSB, Coffee/Tea; Comparator: Continuous intake (12-oz svg/d); Assessment methods and timing: Two 24h dietary recalls (1 weekday and 1 weekend day) via telephone interviews using multiple-pass and portion size estimation aids At baseline, 6mo, and 18mo; Outcomes and assessment methods:; Weight measured using calibrated scale; At baseline, 6mo, and 18mo | Weight change (kg) according to change in juice intake by 1 svg/d, β (95% CI); 6mo: −0.05 (−0.44, 0.27), P=0.71; 18mo: 0.005 (−0.65, 0.65), P=0.99 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Other: intervention group; Limitations:; - Did not account for key confounders: N/A; - No preregistered data analysis plan; Funding:; NHLBI; NIH; Center for Human Nutrition, Johns Hopkins Bloomberg School of Public Health; NICHD
Drapeau, 2004^36^; PCS, Quebec Family Study, Canada; Analytic N=248; Participant characteristics at baseline: Parents and adult offspring; - Age: Mean (SEM): 39.6y (0.9), Range: 18–65y; - Female: 55%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean (SEM): 25.3 (0.3), Range: 17.4–55.6; - Physical activity: NR; - Smoking: NR; - Diet quality: Macro- and micronutrient intakes reported in paper; - TEI: NR; Study beverage intake at baseline: NR; Excluded: missing any dietary data; responding “I don’t know” to any dietary intake category | Exposure: Fruit juice (nonsweet fruit juice: orange, apple, pineapple); Other exposures: SSB, milk; Comparator: Fruit juice intake (categorical change over 6y: more, the same, or less intake); Assessment methods and timing: Three-day dietary record (2 weekdays, 1 weekend day); Represents usual intake; Baseline, 6y; Outcomes and assessment methods:; Weight measured by study personnel. Body fat percentage estimated using underwater weighing technique and the Siri formula. Waist circumference measured by study personnel using Airlie Conference procedures. Sum of 6 skinfold thicknesses (triceps, biceps, medial calf, subscapular, suprailiac, and abdominal) measured by study personnel.; Baseline, 6y | 6y change by 6y change in intake, linear regression; Body fat percentage: NS, Data NR; Waist circumference: NS, Data NR; Sum of 6 skinfold thicknesses: NS, Data NR; 6y change by 6y change in intake, linear regression; Weight change: NS, Data NR | Model adjustments:; - TEI: no; - Key confounders: age, anthropometry at baseline, physical activity; - Other:; Limitations:; - Did not account for key confounders: sex, race/ethnicity, SES, smoking, diet quality; - Did not account for all key confounders; Validation of 3-day dietary record unclear; No information on non-completers; No preregistered data analysis plan; Funding:; Canadian Institutes of Health Research
Duffey, 2010^35^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA) Study, U.S.; Analytic N=2,444; Participant characteristics at baseline: adults; - Age: Mean (SD): 25.0 y (3.6); - Female: 54%; - Race/ethnicity: Black: 47.4%; White: 52.6%; - SEP: NR; - Anthropometry: Mean (SD); BMI: 24.5 (5.0) kg/m2; WC: 77.3 cm (10.9); - Physical activity: Mean (SD): 429 exercise units/wk (302); - Smoking: Current 28.1%, Former 13.1%, Never 58.7%; - Diet quality: NR; - TEI: NR; energy from food, Mean: 2347 kcal; Study beverage intake at baseline: 95% consuming; Among consumers: Mean (SE)=121 (2) kcal/d; Inclusion criteria (original cohort): 18–30y at baseline; White or Black race; permanent residence in one of 4 recruitment sites (Birmingham, AL, Chicago, IL, Minneapolis, MN, Oakland, CA); free of a long-term disease or disability that would interfere substantially with any part of the examination; Excluded from original cohort: pregnant or up to 3 mo post-partum; Excluded from current analyses: people with high WC at baseline or year 7 | Exposure: Fruit juice (does not include sweetened ‘fruit drinks’); Other exposures: Dairy milk, SSB; Comparator: Fruit juice intake (continuous; kcal/d); Fruit juice intake (categorical; quartiles); Assessment methods and timing: Semi-quantitative, interviewer-administered, validated diet history FFQ; Represents previous month At baseline, 7y follow-up (averaged); Outcomes and assessment methods:; WC at minimum abdominal girth measured in duplicate; High WC defined as WC>88cm (women) or >102cm (men); Baseline, 20y follow-up | High WC, Poisson regression, RR (95% CI); Fruit juice intake, categorical: 1.00 (0.92, 1.09), P for trend = 0.999; Fruit juice intake, continuous: 0.98 (0.90, 1.06) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline (body weight), physical activity, diet quality (fruit, vegetables, milk, non-milk dairy), smoking; - Other: Calories from alcohol, CARDIA exam center; Limitations:; - Did not account for key confounders: socioeconomic position, anthropometry at baseline (WC); - Start of follow-up and exposure do not coincide; Unclear if exposure assessment tool is validated; Impact of missing data on analysis unclear; No preregistered data analysis plan; not all key confounders accounted for; Funding:; Danone Research Center; NIH; UNC-CH Center for Environmental Health and Susceptibility; UNC-CH Clinic Nutrition Resarch Center; Carolina Population Center; University of Alabama at Birmingham Coordinating Center; University of Alabama at Birmingham Field Center, University of Minnesota Field Center, Northwestern University Field Center, Kaiser Foundation Research Institute
Ferreira-Pego, 2016^37^; PCS of trial data, PREDIMED (PREvención con DIeta; MEDiterránea), Spain; Analytic N=1,868; Participant characteristics at baseline: adults at high risk for CVD; - Age: Mean (SD): 67y (6); - Female: 53%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean (SD): 28.3 (3.5) kg/m2; - Physical activity: Leisure time MET, min/d, Mean (SD): 274 (252); - Smoking: Never: ~58%; Current; ~17%; Former: ~26%; - Diet quality: Mean (SD), g/d; Vegetables: ~334 (152); Fruit: ~359 (199); - TEI: Mean (SD): 2,323 (~530) kcal/d; Study beverage intake at baseline: During follow up: Mean 29.3 mL/d; Inclusion criterion: high-risk for CVD Excluded: MetS, history of CVD, severe chronic illness, drug/alcohol addiction, history of allergy or intolerance to olive oil or nuts, low predicted likelihood of changing dietary habits, missing dietary data, implausible TEI | Exposure: Fruit juice (natural fruit juices: freshly extracted juice, for which the only procedure accepted was the squeezing of the whole piece of fruit); 1svg=200mL; Other exposures: SSB, LNCSB; Comparator: Categorical intake: <1 svg/wk, 1–5, >5; Outcomes and assessment methods:; - Weight: measured by trained personnel with calibrated scales; - Height: measured by trained personnel with a wall-mounted stadiometer.; - Waist circumference measured using an anthropometric tape midway between the lower rib and the superior border of the iliac crest; - Abdominal obesity: waist circumference ≥88cm in women and ≥102 cm in men Baseline, annually for ≥2y | Abdominal obesity, Multivariable time-dependent; Cox proportional regression, HR (95% CI) Natural fruit juices:; <1 svg/wk: Ref; 1–5 svg/wk: 0.97 (0.76, 1.24); >5 svg/wk: 1.52 (1.02, 2.25); P for trend: 0.08 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (vegetables, legumes, fruit, cereals, meat, fish, bakery, dairy products, olive oil, and nuts); - Other: alcohol (overall alcohol intake & alcohol squared in grams per day), intervention group, prevalence of MetS components at baseline; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - No information on whether or not amount of missing data varied across exposure groups; Follow-up time differs among participants; No preregistered data analysis plan; Funding:; Spanish Ministry of Health, the Thematic Network, FEDER (European Regional Development Fund), the Centre Catalá de la Nutrició de l’Institut d’Estudis Catalans, and the Fundació “LaMarat´ o de TV3”
Funtikova, 2015^38^; PCS, Spain; Analytic N=2,112; Participant characteristics at baseline: adults; - Age: Mean: ~49.2y; - Female: 53%; - Race/ethnicity: NR; - SEP: Higher education ~37%; - Anthropometry: Mean: WC, ~89.6 cm; - Physical activity: Mean: ~200 MET-min/d (leisure time); - Smoking: Current smoker ~26%; - Diet quality: validated, modified Mediterranean Diet Score (mMDS), mean ~17.6 (out of a possible 30); - TEI: Mean: ~11.2 MJ/d; Study beverage intake at baseline: Juices, mL/d, mean (SD): 64 (114); Inclusion criteria (original cohort, n=3058): adults aged 25–75y residing in Girona, Spain; Excluded from current analyses: no longer residing in catchment area (n=343); lost to follow-up (n=534), missing data for WC (n=37) and smoking status (n=32) | Exposure: Including commercial and natural fruit and vegetable juices; apple, peach, orange, grape, and tomato (1 svg=200mL); Other exposures: SSB, Dairy milk; Comparator: Juice intake (continuous; 100 kcal/d); Juice intake (categorical; svg/d): No consumption (ref), <1, ≥1; Juice intake (categorical; change in consumption): No consumption (ref), Decrease, Increase, Maintain; Assessment methods and timing: Validated, 166-item FFQ administered by trained interviewer; Represents intake during previous year Baseline, 9y follow-up; Outcomes and assessment methods:; WC measured midway between lowest rib and iliac crest with participant lying horizontally. Abdominal obesity defined as >102 cm for men and >88 cm for women; Baseline, 9y follow-up | Abdominal obesity, OR (95% CI), logistic regression; Juices, categorical; Incidence by baseline intake:; No consumption (ref); <1 svg/d: 0.98 (0.72, 1.31); ≥1 svg/d: 0.74 (0.49, 1.13); Men (n=756); No consumption (ref); <1 svg/d: 1.15 (0.72, 1.82); ≥1 svg/d: 1.23 (0.64, 2.36); P trend =0.62; Women (n=723); No consumption (ref); <1 svg/d: 0.87 (0.60, 1.30); ≥1 svg/d: 0.53 (0.35, 1.00); P trend = 0.027; WC, cm, Mean (95% CI), linear regression; Juices, continuous; Change per 100 kcal/d increase: −0.03 (−0.74, 0.68), P=0.93; Men: −0.25 (−1.26, 0.76), P=0.63; Women: 0.06 (−0.95, 1.07), P=0.91; WC, cm, Change by change in consumption, Juices (change in consumption), categorical, Mean (95% CI), linear regression:; No consumption (ref); Decrease: 0.25 (−0.67, 1.17), P=0.59; Increase: 0.25 (−0.73, 1.22), P=0.62; Maintain: 0.15 (−1.93, 2.24), P=0.89; Men (n=1000); No consumption (ref); Decrease: 0.50 (−0.71, 1.72), P=0.42; Increase: −0.81 (−2.10, 0.48), P=0.22; Maintain: 0.30 (−2.05, 2.56), P=0.60; Women (n=1112); No consumption (ref); Decrease: 0.10 (−1.35, 1.56), P=0.69; Increase: 1.05 (−0.40, 2.51), P=0.16; Maintain: 0.38 (−1.80, 2.55), P=0.74 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Other: energy under- or over-reporting; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Start of follow-up and exposure do not coincide; High attrition (31%) with no information on non-completers; No preregistered data analysis plan; Not all key confounders accounted for; Funding:; Catalan Government; Carlos III Health Institute European Fund for Regional Development; Catalonian Agency for the Administration of University and Research Grants
Halkjaer, 2009^39^; PCS, Danish Diet, Cancer, and Health study, Denmark; Analytic N=42,696; Participant characteristics at baseline: adults; - Age: 56y (Range: 50–64y); - Female: 53%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean: 25 kg/m2; - Physical activity: Perform ≥30min sport/wk; - Smoking: Current: 33%; - Diet quality: Median (5th-95th %), kcal/d; Vegetables: Male(M): 67 (22–146); Female(F): 74 (24–169); Fruits: M: 84 (16–277); F: 114 (25–320); Soft drinks: M: 6.8 (0.1–81); F: 2.0 (0.1–35); - TEI: NR; Study beverage intake at baseline: Total juice: Median (5th-95th %), kcal/d; Males: 3.6 (0.0–43); Females: 3.8 (0.1–45); Inclusion criteria: Age 5–64y, born in Denmark, no history of cancer; Excluded: too many data errors, missing data on follow-up time | Exposure: Vegetable and fruit juice; Other exposures: SSB, Coffee/Tea; Comparator: Continuous intake (per 60 kcal/d increments); Assessment methods and timing: Validated FFQ; represents usual intake Baseline; Outcomes and assessment methods:; - Height, weight, waist circumference, hip circumference measured at baseline; - Follow-up weight and WC were self-report; - Waist circumference measured at the smallest horizontal circumference between the ribs and iliac crest (the natural waist), or, in case of an indeterminable waist narrowing, halfway between the lower rib and the iliac crest; SELF-REPORTED: measuring tape was provided, participants were told to measure WC at the level of the umbilicus; - Hip circumference was measured at the largest horizontal expansion of the buttocks; Baseline, 5y follow up | Waist circumference, cm, 5y change per 60 kcal/d juice, Linear regression, β (95% CI); Women: −0.15 (−0.38, 0.09); Men: 0.11 (−0.09, 0.31); Interaction, P=0.09 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking; - Other: Alcohol; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, diet quality; - Attrition 25% without information on non-completers, Exposure data only measured at baseline, WC self-reported, No preregistered data analysis plan; no reporting of other outcomes measured (weight, BMI, hip circumference); Funding:; National Danish Research Foundation; Diet, Obesity and Genes project, supported by European Community
Hosseinpour-Niazi, 2021^41^; PCS, Tehran Lipid and Glucose Study, Iran; Analytic N=1,915; Participant characteristics at baseline: adults; - Age: Mean (SD): 36.5 (13.3)y; - Female: 60%; - Race/ethnicity: NR; - SEP: Baseline characteristics reported across tertiles (T1 and T3) of 100% juice intake; % with academic degrees: T1: 31.8%, T3: 21.6%, p<0.001; Occupational status, % unemployed: T1: 54.4%, T3: 60.5%, p=0.073; - Anthropometry: BMI, mean (SD): 25.6 (4.5) kg/m2; - Physical activity: MET-h/week, mean (SD): T1: 4.6 (0.3), T3: 5.5 (0.3), p=0.061; - Smoking: % smoker at baseline: T1: 12.4%, T3: 33.1%, p<0.001; - Diet quality: NR; - TEI: Kcal/day, mean (SD); T1: 2296 (35); T3: 2407 (35); p=0.041; Study beverage intake at baseline: Mean (SD): 24.7 (0.9) g/day; Median intake, g/d: T1: 2.9, T3: 29.6; Inclusion criteria: age ≥3y at baseline, resident of district 13 in Tehran; Excluded: refusal to complete FFQ (n=838), incomplete FFQ information (n=197), metabolic syndrome at baseline (n=879), pregnant or lactating at baseline or follow-up (n=28), daily energy intake < 500 and >4200 kcal/d (n=115), on a specific diet for hyperlipidemia, hypertension, or hyperglycemia (n=26), missing laboratory or anthropometric data related to metabolic syndrome diagnosis during follow-up (n=309) | Exposure: 100% fruit juices included cantaloupe juice (with pulp), apple juice (without pulp), grapefruit juice (without pulp), and orange juice (without pulp); Other exposures: SSB; Comparator: Categorical intake (tertiles); Assessment methods and timing: Validated semi-quantitative FFQ; represents intake over previous year. Standard units or portion sizes were converted to grams.; 2006–2008 (baseline), 2008–2011, 2012–2015, 2016–2018; Outcomes and assessment methods:; Height and weight: valid measure by study staff. BMI calculated from weight and height.; % weight change calculated by subtracting baseline weight from follow-up weight, divided by baseline weight, and multiplied by 100.; Participants categorized as those who lost weight (≥-2%), those with weight stability (−1.9%-1.9%), and those who gained weight (≥2%).; 2006–2008, 2016–2018 (median follow-up: 8.91y (IQR: 7.98–9.69y)) | Risk of weight gain ≥2%, multivariable Cox regression, HR (95% CI); T1: ref; T2: 0.90 (0.77, 1.05); T3: 1.41 (1.20, 1.65); p<0.001 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position (education levels, occupation status), anthropometry at baseline, physical activity, diet quality (SSB, dietary fiber), smoking; - Other: Family history of diabetes, anti-hyperglycemic medication use, antihyperlipidemic medication use, dietary cholesterol; Limitations:; - Did not account for key confounders: race and/or ethnicity,; - Start of follow-up and exposure do not coincide; High amount of missing data; No preregistered data analysis plan; Funding:; Research Institute for Endocrine Sciences, Shahid Beheshti University of Medical Sciences, Tehran, Iran
Konieczna, 2019^42^; PCS, Secondary analysis of PREDIMED trial, Spain; Analytic N=7,009; Participant characteristics at baseline: Spanish older adults; - Age: Mean (SD): 67y (6.2); - Female: 58%; - Race/ethnicity: All “white, elderly Spanish”; - SES: Higher education/technician: 7%; - Anthropometry: Body weight, kg, mean (SD): 76.7 (12.0); WC, cm, mean (SD): 100 (10); BMI, kg/m^2, mean (SD): 30.0 (3.8); Obesity prevalence: 47%; Abdominal obesity prevalence: 73%; - Physical activity: METs (min/d), mean (SD): 233 (239); - Smoking: Current smoker: 14%; - Diet quality: Adherence to MedDiet (14-points score), mean (SD): 9 (2); - TEI: Kcal/day, mean (SD): 2239 (543); Study beverage intake at baseline: mean (SD): 0.14 (0.33) svg/d; Average yearly change (svg/d) during follow-up, mean (5th, 95th percentile): −0.01 (−0.22, 0.22); Inclusion criteria: age between 55–80y, free of CVD at enrollment but at risk of CVD based on T2DM diagnosis or ≥3 risk factors (hypercholesterolemia, low HDL, overweight/obesity, hypertension, current smoking or family history of premature coronary heart disease); Excluded: missing data on waist circumference, physical activity, or FFQ at baseline (n=291), total energy intake values outside predefined limits (500–3500 kcal/d (women), 800–4000 kcal/d (men)) (n=147) | Exposure: 100% juice (natural fruit juices). Exposure of interest was change in intake expressed in serving/d, calculated as the difference between yearly measured values and values from the previous year.; Other exposures: Milk, SSB, LNCSB, coffee and tea; Comparator: Different intake of 100% juice (continuous, svg/d); Assessment methods and timing: 137-item semi-quantitative FFQ; intake calculated by multiplying serving size by frequency of consumption (from never to > 6 times/d); At baseline and yearly thereafter (~5y follow-up); Outcomes and assessment methods:; Height and weight: valid measure by study staff; BMI: calculated from height and weight measurements; Waist circumference: determined midway between lowest rib and iliac crest using anthropometric tape; measured in duplicate by trained staff; average of two measurements was analyzed value; Absolute change in body weight and WC: calculated as difference between yearly measured values and values from previous year; Baseline and annually thereafter (mean follow-up 4.8y) | ΔWC (cm) over 5y follow-up by concurrent changes in juice intake (svg/d), β (95% CI), generalized estimating equation; Overall: −0.20 (−0.53, 0.13), p=0.235; Men: −0.10 (−0.48, 0.28), p=0.605; Women: −0.28 (−0.76, 0.21), p=0.259; ΔBody weight (kg) over 5y follow-up by concurrent changes in juice intake (svg/d), β (95% CI), generalized estimating equation 0.02 (−0.14, 0.19), p=0.779 | Model adjustments:; - TEI: Yes (for food groups found to be significantly associated with outcomes); - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking, diet quality; - Other: Time (years, due to slight variations in period between successive visits), center, intervention group (combined MedDiets vs. control); for food groups for which the associations with changes in anthropometry were statistically significant, models were additionally adjusted for intake of other foods simultaneously, to estimate mutually adjusted associations. No multi-collinearity was observed between these food groups.; Limitations:; - Did not account for key confounders: race and/or ethnicity; - No preregistered data analysis plan; Limited generalizability; Funding:; CIBER Fisiopatología de la Obesidad y Nutrición (CIBEROBN); Instituto de Salud Carlos III (ISCIII); “FOLIUM” program within the FUTURMed project; Fundación Instituto de Investigación Sanitaria Illes Balears; ERC Advanced Research Grant
Mozaffarian, 2011^43^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-Up Study (HPS), U.S.; Analytic N: NHS = 50,422, NHS II = 47,898, HPS = 22,557; Participant characteristics at baseline: Adults; - Age: Mean (SD):; NHS 52.2y (7.2), NHS II 37.5y (4.1), HPS; 50.8y (7.5); - Female: NHS & NHS II: 100%; HPS: 0%; - Race/ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: Mean (SD): BMI (kg/m2), NHS 23.7 (1.4), NHS II 23.0 (2.7), HPS 24.7 (1.1); - Physical activity: MET-hr/wk, Mean (SD): NHS 14.8 (9.9), NHS II 21.6 (25.9), HPS 22.9 (15.1); - Smoking: Never smoker: 53%, Past smoker: 33%, Current smoker: 13%, Missing: 1%; - Diet quality: Mean, svg/d; Fruit: ~1.5; Vegetables: ~3.5; Whole grains: ~0.6; Additional food group data in paper; - TEI: NR; Study beverage intake at baseline: NR; Excluded: obesity, diabetes, cancer, or cardiovascular, pulmonary, renal, or liver disease at baseline; missing data on lifestyle habits; implausible energy intake, >9 blank responses on the diet questionnaire; newly pregnant during follow-up; >65y of age | Exposure: 100% fruit juice intake (apple juice or cider, orange, grapefruit, and other fruit juice); Other exposures: Milk, SSB, LNCSB; Comparator: Continuous intake (svg/d); Assessment methods and timing: Validated questionnaire; represents usual dietary intake; At baseline, every 4y over 12- to 20-y follow-up; Outcomes and assessment methods:; - Weight was collected via self-report from questionnaire; - At baseline, and every 2y over 12- to 20-y follow-up | Weight, lb, Linear regression, β (95% CI) Change per svg/d increase:; NHS: 0.26 (0.20, 0.32), P<0.001; NHS II: 0.49 (0.41, 0.58), P<0.001; HPS: 0.17 (0.10, 0.25), P<0.001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, whole-fat and low-fat dairy, potato chips, potatoes/fries, whole grains, refined grains, sweets and desserts, processed and unprocessed meats, trans fat, fried foods at and away from home, and other beverage types); - Other: Alcohol, television watching, sleep duration; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Not all key confounders accounted for; Self-reported weight; Funding:; NIH; Searle Scholars Program
Pan, 2013^44^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-up Study (HPS), U.S.; Analytic N: NHS = 50,013; NHS II = 52,987; HPS = 21,988; Participant characteristics at baseline: Adults; - Age: Mean ~47y; - Female: NHS & NHS II: 100% HPS: 0%; - Race/ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: Overweight: 31%, Obesity: 17%, BMI Mean: ~25 kg/m2; - Physical activity: Mean~18 MET-hr/wk; - Smoking: Never smoker: 54%, Past smoker: 33%, Current smoker: 13%; - Diet quality: Mean, serv/d; SSB: ~0.4; - TEI: NR; Study beverage intake at baseline: Fruit juice intake, svg/d, Mean (5th-95th%): NHS 0.83 (0–2.29), NHS II 0.62 (0–2.0), HPS 0.78 (0–2.43) | Exposure: Fruit juice intake (apple, orange, grapefruit, and other juice); Other exposures: Milk, SSB, LNCSB, Coffee/Tea; Comparator: Continuous intake (svg/d); Assessment methods and timing: Validated FFQ; represents usual intake of foods and beverages At baseline, every 4y over 16- to 20-y follow-up; Outcomes and assessment methods:; Weight was collected via self-report from questionnaire; At baseline, and every 2y over 16- to 20-y follow-up | Weight change over ~20y (by 4-year assessment intervals), kg, Linear regression, β (95% CI) Change per svg/d increase over each 4y period:; NHS: 0.24 (0.20, 0.28), P=NR; NHS II: 0.26 (0.22, 0.30), P=NR; HPS: 0.15 (0.10, 0.19), P=NR; Stratified by age: ≤50y, >50y; NHS: 0.23 (0.15, 0.31), 0.42 (0.38, 0.46), P=0.24; NHS II: 0.28 (0.24, 0.32), 0.19 (0.09, 0.29), P=0.04; HPS: 0.15 (0.07, 0.23), 0.15 (0.09, 0.20), P=0.76; Stratified by BMI (kg/m2): <25, 25–29.9, ≥30; NHS: 0.07 (0.03, 0.10), 0.26 (0.19, 0.320, 0.60 (0.47, 0.74), P<0.001; NHS II: 0.13 (0.09, 0.16), 0.33 (0.25, 0.41), 0.55 (0.42, 0.68), P<0.001; HPS: 0.06 (0.01, 0.11), 0.16 (0.10, 0.23), 0.55 (0.32, 0.79), P<0.001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, whole grain, refined grain, potatoes, potato chips, red meat, other dairy products, sweets and deserts, nuts, fried foods, and trans fat, and other beverage types); - Other: Alcohol, protein, television watching; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Not all key confounders accounted for; Self-reported weight; Funding:; NIH
Rautiainen, 2015^45^; PCS of trial data, Women’s Health Study, US; Analytic N=18,146; Participant characteristics at baseline: Women ≥45y with normal BMI at baseline; - Age: Mean: 53y, all ≥45y; - Female: 100%; - Race/ethnicity: “Predominantly Caucasian”; - SEP: “Predominantly health care professionals”; - Anthropometry: BMI 18.5-<25 kg/m2; - Physical activity: Mean~17 MET hrs; - Smoking: Current: 14.5%; - Diet quality: Fruits & vegetables, svg/d; Quintile 1: <3.5,; Q2: 3.5-<4.9,; Q3: 4.9-<6.3; Q4: 6.3-<8.2,; Q5: ≥8.3; - TEI: Mean: 1,710 kcal/d; Study beverage intake at baseline: Fruit juice intake (svg/d): Quintile 1 (Q1)<0.1, 23%; Q2: 0.1 to <0.3, 18%; Q3: 0.3 to <0.5, 20%; Q4: 0.5 to <0.8, 20%; Q5: ≥0.8, 19%; Inclusion criteria: ≥45y, postmenopausal or not planning pregnancy, no history of myocardial infarction, stroke, transient ischemic attack, cancer, diabetes, or CVD; Excluded: BMI outside 18.5–25kg/m2, missing fruit/vegetable intake data, insufficient FFQ data, implausible TEI | Exposure: Fruit juice (grapefruit, orange, apple, and other juice; does not specifically say ‘100%’); Other exposures: None; Comparator: Categorical (quintiles); Outcomes and assessment methods:; - At baseline, and 2, 3, 5, 6, 9y follow-up during RCT, then annually from 11–17y during observational follow-up (Mean follow-up: 15.9y); - Weight (lb) and height (inches) were self-reported; - BMI calculated as kg/m2; - Overweight: BMI 25 to <30 kg/m2; - At baseline, and 2, 3, 5, 6, 9y follow-up during RCT, then annually from 11–17y during observational follow-up (Mean follow-up: 15.9y) | Incident overweight/Obesity (BMI ≥25 kg/m2), among normal BMI at baseline, Cox proportional hazard, HR (95% CI); Q1 (n=4130): ref; Q2 (n=3287): 0.98 (0.91, 1.04); Q3 (n=3615): 0.79 (0.73, 0.84); Q4 (n=3573): 0.88 (0.82, 0.95); Q5 (n=3518): 0.81 (0.76, 0.88); P-trend <0.0001 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking; - Other: Randomization treatment assignment, history of hypercholesterolemia or hypertension, postmenopausal status, postmenopausal hormone use, supplements, alcohol; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, diet quality; - Not all key confounders accounted for; Exposure not clearly defined; Exposure measured only at baseline; Attrition 54% without information on non-completers; Weight and height self-reported; No preregistered data analysis plan; Funding:; NIH; Swedish Council of Working Life and Social Research
Romaguera, 2011^46^; PCS, European Prospective Investigation into Cancer and Nutrition (EPIC), Italy, UK, the Netherlands, Germany, Denmark; Analytic N=48,631; Participant characteristics at baseline: Adults; - Age: 20–60y; - Female: 60%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - Diet quality: Mean (SD), g/d; Fruits: ~180; Vegetables: ~170; Soft drinks: ~900; - TEI: NR; Study beverage intake at baseline: Juice intake, g/d, Mean (SD): Men, 63.76 (117.91), Range=31.19–189.97; Women, 76.50 (128.63), Range=35.24–119.77; Excluded: no blood sample data, pregnancy, missing diet or anthropometric data, highest and lowest 1% of TEI:energy requirement ratio, chronic disease (cancer, CVD, diabetes) at baseline or follow up, unrealistic anthropometric measurements, baseline age >60y or follow-up age >65y, missing data on smoking or change in smoking status from baseline to follow up | Exposure: 100% fruit juice; Other exposures: Milk, SSB, Coffee/Tea; Comparator: Continuous, 100 kcal/d; Assessment methods and timing: Country-specific validated FFQ; represents usual food intakes Baseline; Outcomes and assessment methods:; - Weight and height measured using standard protocol or via self-report; - Waist circumference (WC) measured either midway between the lowest rib and iliac crest, at the narrowest torso circumference, or via self-report; - BMI calculated as weight (kg) divided by height (m) squared; - Waist circumference for a given body mass index (WCBMI) calculated as the residual values from gender- and center-specific regression equations of WC on BMI using baseline and follow-up values of WC and BMI; Baseline, 5.5y follow up | Association between intake and annual change in WC for given BMI; β2 (95% CI), Linear regression; All: −0.01 (−0.03, 0.00), P=0.100; Men: −0.01 (−0.02, 0.01), P=0.315; Women: −0.02 (−0.05, 0.01), P=0.211; Interaction by gender: P=NS | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race/ethnicity, SEP, anthropometry at baseline, physical activity, smoking; - Other: Alcohol, follow-up duration, menopausal status and hormone replacement therapy use (in women); Limitations:; - Did not account for key confounders: Diet quality; - Exposure measured at baseline only; excluded participants with chronic disease at follow up; Funding:; European Union; Danish Strategic Research Council
Schulze, 2004^47^; PCS, Nurses’ Health Study II, U.S.; Analytic N=51,603; Participant characteristics at baseline: Adult female nurses; - Age: Mean ~36y (24–44y); - Female: 100%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~24.4 kg/m2; - Physical activity: ~19 METs/wk; - Smoking: 12% current smokers; - Diet quality: Cereal fiber: ~5.5 g/d; Total fat intake: ~31% of total energy intake; - TEI: Mean ~1800 kcal/d; Study beverage intake at baseline: NR; Inclusion criteria: female nurses aged 24 to 44y at study initiation (1989); Excluded: missing dietary questionnaire in 1991 or >9 items on FFQ left blank; implausible total energy intake (< 500 kcal/d or >3500 kcal/d); history of diabetes, cancer (except nonmelanoma skin cancer), or CVD at baseline; no data on physical activity in 1991 questionnaire, missing SSB intake information, history of diabetes or CVD before 1995 or reported cancer diagnosis (except nonmelanoma skin cancer) on any questionnaire, missing body weight information, no data on physical activity assessed in 1997 | Exposure: Fruit juice (apple, orange, grape, and other juice); Other exposures: SSB, 100% juice; Comparator: Categorical intake: Change in drink frequency from 1991 to 1995): Consistent ≤1/wk, Consistent ≥1/d, Increased (≤1/wk to ≥1/d), Decreased (≥1/d to ≤1/wk), Other; Assessment methods and timing: Validated semi-quantitative FFQ; represents intake over previous year Baseline (1991), 4y follow-up (1995); Outcomes and assessment methods:; Height measured via self-report at baseline only, Weight measured via self-report. BMI calculated as kg/m2 Baseline (1991), 4y follow-up (1995) | Weight gain, Per change in 100% juice consumption from 1991–1995:; Increased intake (≤1/wk to ≥1/d): 4.03 kg; Decreased intake (≥1/d to ≤1/wk): 2.32 kg P<0.001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, diet quality (cereal fiber intake, total fat intake), smoking; - Other: Postmenopausal hormone use, oral contraceptive use; Limitations:; - Did not account for key confounders: Race and/or ethnicity, socioeconomic position; - Not all key confounders accounted for; High attrition without information on non-completers; Weight and height self-reported; No preregistered data analysis plan; Funding:; NIH; European Association for the Study of Diabetes/American Diabetes Association; German Academic Exchange Service (DAAD)
Siqueira, 2023^50^; PCS, ELSA-Brazil cohort, Brazil; Analytic N=6,124; Participant characteristics at baseline: adults, older adults; - Age: mean age 50 ± 8.5y; - Female: 59%; - Race/ethnicity: White: 50.5%; Non-white: 49.5%; - SEP: income per capita ($): 876 ; Education: 53% college, 37% secondary, 10% elementary; - Anthropometry: Mean BMI 24.9 ± 3.8 kg/m2; - Physical activity: Strong (1,500 MET-min/wk high intensity or 7 days of any combination of high and moderate reaching 3,000 METS-min/wk): 8%; Moderate (>3days of 20 min high intensity exercise or >5 days 30 min moderate intensity: 16%; Weak (no exercise): 76%; - Smoking: Non-smokers: 11%; Former: 19%; Current: 69.5%; - Alcohol intake: Mean intake g/d: Fruit: 491; Vegetables: 183; - TEI: mean 2,943; Study beverage intake at baseline: SSB consumption servings/d:; <0.1: 64%; >0.1-<0.4: 20%; >0.4-<1: 10%; >1: 6%; Excluded: history of cardiovascular events and cancer at baseline, reported intake of diet soda, implausible calorie intake (<500 and >600 kcal/d), history of bariatric surgery, lack of follow-up, missing data on main exposure or outcome | Exposure: 100% fruit juice, fruit or fruit pulp with or without addition of water; Comparator: daily beverage intake: < 0.1 serving/d, >0.1 to < 0.4 serving/day, > 0.4 to < 1 serving/day, and = 1 servings/day; Assessment methods and timing: Validated semi-quantitative FFQ; average daily intake calculated from frequency of servings equivalent to 250ml; Baseline (2008–2010); Outcomes and assessment methods:; Height was measured using a vertical wall stadiometer Seca-SE-216 (Seca Brasil, Brazil) with an accuracy of 1 mm, Body weight was measured using a calibrated Toledo 2096PP scale (Toledo do Brasil Ltda, Brazil), BMI calculated as body weight divided by height squared (kg /m2), WC measured with measuring tape around midpoint between the lower edge of the ribs and the iliac crest Follow-up (2012–2014) | Risk of high WC: relative risk (95% CI), poisson regression , 1 serving=250mL; Model 2:; <0.1 serving/d: REF; 0.1-<0.4/d: 1.09 (0.85–1.39); 0.4-<1/d: 0.99 (0.77–1.27); >1/d: 1.26 (0.90–1.78); Model 3 (controlled for TEI); <0.1 serving/d: REF; 0.1-<0.4/d: 1.11 (0.86–1.41); 0.4-<1/d: 1.05 (0.81–1.34); >1/d: 1.39 (0.97–1.91) | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, race, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Other:; Limitations:; - Did not account for key confounders:; - Exposure data only measured at baseline; no information on non-completers; No preregistered data analysis plan; Funding:; Brazilian Ministry of Health (Department of Science and Technology) and Ministry of Science, Technology and Innovation, FINEP (Financiadora de Estudos e Projetos), National Council for Scientific and Technological Development

a Abbreviations: AHA: American Heart Association; BMI: body mass index; BP: blood pressure; d: day(s); CARDIA: Coronary Artery Risk Development in Young Adults; CBC: complete blood count; CGJ: concord grape juice; CHF: congestive heart failure; cm: centimeter(s); CVD: cardiovascular disease; DASH: Dietary Approaches to Stop Hypertension; dL: deciliter(s); FFQ: food frequency questionnaire; g: gram(s); HDL-C: high-density lipoprotein cholesterol; HEI: Healthy Eating Index; hr: hour(s); HPS: Health Professionals Follow-up Study; HR: hazard ratio; in: inch(es); K: kelvin; kcal: kilocalories; kg: kilograms; kJ: kilojoules; LDL-C: low-density lipoprotein cholesterol; LNCSB: low- and no-calorie sweetened beverage(s); MET: metabolic equivalents of task; MetS: metabolic syndrome; mg: milligram(s); min: minute(s); MJ: megajoule; mL: milliliters; mm: millimeters; mmHg: millimeters of mercury; mo: month(s); MUFA: monounsaturated fatty acids; N/A: not applicable; NCEP: National Cholesterol Education Program; NHLBI: National Heart, Lunch, and Blood Institute; NHS: Nurses Health Study; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIH: National Institutes of Health; NR: not reported; NS: not significant; NSAID: non-steroidal anti-inflammatory drug; OJ: orange juice; OR: odds ratio; oz: ounce; PCS: prospective cohort study; PREDIMED: PREvención con DIeta MEDiterránea; PUFA: polyunsaturated fatty acids; PVD: peripheral vascular disease; RCT: randomized controlled trial; ref/REF: reference; SD: standard deviation; SEM: standard error of mean; SEP: socioeconomic position; SFA: saturated fatty acids; SSB: sugar-sweetened beverage(s); svg: serving; T2DM: type 2 diabetes mellitus; TEI: total energy intake; UNC-CH: University of North Carolina-Chapel Hill; WBC: white blood cells; WC: waist circumference; wk: week(s); wt: weight; y: year(s)

Table 15 Risk of bias for randomized controlled trials examining 100% juice consumption in adults and body composition and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Aptekmann, 2010^30^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Hollis, 2009^40^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
Shenoy, 2010^48^ | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Silver, 2011^49^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 16 Risk of bias for observational studies examining 100% juice consumption in adults and body composition and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Auerbach, 2018^31^ | LOW* | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Bes-Rastrollo, 2008^32^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Castellana, 2020^33^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | LOW | HIGH | VERY HIGH
Chen, 2009^34^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Drapeau, 2004^36^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Duffey, 2010^35^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ferreira-Pego, 2016^37^ | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Funtikova, 2015^38^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Halkjaer, 2009^39^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Hosseinpour-Niazi, 2021^41^ | SOME CONCERNS | LOW | HIGH | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Konieczna, 2019^42^ | LOW* | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Mozaffarian, 2011^43^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Pan, 2013^44^ | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Rautiainen, 2015^45^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Romaguera, 2011^46^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Schulze, 2004^47^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Siqueira, 2023^50^ | LOW* | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. *Low risk of bias except for concerns about uncontrolled confounding.

Table 17 Evidence examining the relationship between 100% juice consumption in individuals during pregnancy and gestational weight gain^a^

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
Guilloty, 2015^51^; PCS, Puerto Rico Testsite for Exploring Contamination Threats (PROTECT), U.S.; (Puerto Rico); Analytic N=160; Participant characteristics at baseline:; Puerto Rican individuals during pregnancy; - Age: Mean (SD) = 27.4 (5.3) y; - Female: 100%; - Race/ethnicity: NR; - SEP: Education: 84% > high school, 16%≤ high school; Income: 40% <$20,000 family annual income (poverty threshold for 2012 in Puerto Rico), 60% ≥$20,000. 14% nonresponse rate for income reporting.; - Anthropometry: Pre-pregnancy BMI: 6% with underweight, 50% with normal weight, 25% with overweight, 19% with obesity; - Physical activity: NR; - Smoking: NR; - Alcohol intake: NR; - TEI: NR; Study beverage intake at baseline:; 100% juice <1/day ~52%; Inclusion criteria: Healthy pregnant women 18-40y, living in northern karst region of Puerto Rico, planning to give birth in one of the three participating hospitals, having less than 20 wk gestation, no pregnancy complications, completion of FFQ. Exclusion criteria: prepregnancy use of birth control pills; pregnancy conceived by use of assistive reproductive technology and; conditions or complication such as diabetes, hypertension, or heart disease. | Exposure: 100% fruit juice. Serving size NR.; Other exposures: milk, coffee, soft drinks, fruit drinks; Comparator: Categorical intake (<1/d, ≥1/d); Assessment methods and timing: Validated, self-administered, semiquantitative FFQ; represents intake during previous 12mo; Between second and third prenatal visit (20-28wk); Outcomes and assessment methods:; GWG calculated from difference between last and initial weight (first prenatal visit at 16-20wk) recorded in medical record. Participants were classified as “inadequate GWG” if weight gain was below, “appropriate GWG” if weight gain was according, and “excessive GWG” if weight gain was above the IOM 2009 guidelines.; Last prenatal visit before delivery | [underlined: Gestational weight gain], Chi-square difference; Total Sample; Excessive GWG: 23.5% <1/d vs 25.7% ≥1/d; Appropriate GWG: 51.8% <1/d vs 48.6% ≥1/d; Inadequate GWG: 24.7% <1/d vs 25.7% ≥1/d; P=0.92; Stratified by pre-pregnancy BMI (Under & Normal weight):; Excessive GWG: 7.3% <1/d vs. 17.0% ≥1/d; Appropriate GWG: 58.5% <1/d vs. 55.3% ≥1/d; Inadequate GWG: 34.1% < 1/d vs. 27.7% ≥1/d; P=0.15; Stratified by pre-pregnancy BMI (with overweight and obesity):; Excessive GWG: 38.6% <1/d vs. 40.7% ≥1/d; Appropriate GWG: 45.5% <1/d vs. 37.0% ≥1/d; Inadequate GWG: 15.9% < 1/d vs. 22.2% ≥1/d; P=0.47 | Model adjustments:; - TEI: no; - Key confounders: anthropometry at baseline, diabetes mellitus in the current pregnancy (exclusion criteria), hypertensive disorders in the current pregnancy (exclusion criteria); - Other: N/A; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, physical activity, smoking, diet quality, parity; - Exposure not well defined; Exposure data only measured once; Low response rate for completing and returning FFQ, differences in FFQ completers vs. noncompleters (completeres were younger and with higher education and income); No preregistered data analysis plan; Funding:; Superfund Research for the National Institute of Environmental Health Sciences; RCMI Clinical Research Center; Center for Collaborative Research in Health Disparities; Puerto Rico Clinical and Translational Research Consortium; NIH Institute of Minority Health and Health Disparities

a Abbreviations: BMI: body mass index; FFQ: food frequency questionnaire; GWG: gestational weight gain; IOM: Institude of Medicine; mo: months; N/A: not applicable; NIH: National Institutes of Health; NR: not reported; PCS: prospective cohort study; RCMI: Research Centers in Minority Institutions; SD: standard deviation; T2DM: type 2 diabetes mellitus; TEI: total energy intake; wk: week(s); y: year(s)

Table 18 Risk of bias for observational study examining 100% juice consumption in individuals during pregnancy and gestational weight gain^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Guilloty, 2015^51^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )

Table 19 Evidence examining the relationship between 100% juice consumption in individuals during postpartum and postpartum weight change^a^

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
Alderete, 2020^52^; PCS, Southern California Mother’s Milk Study, U.S.; Analytic N=99; Participant characteristics at baseline:; Postpartum women; - Age: Mean (SD): 29.4 (6.5)y; - Female: 100%; - Race/ethnicity: 100% self-identified as Hispanic (inclusion criteria); - SEP: NR; - Anthropometry: Weight, kg, mean (SD): 73.1 (13.1); BMI, kg/m2, mean (SD): 29.8 (4.8); pre-pregnancy: 29% healthy weight, 38% overweight, and 32% with obesity; - Physical activity: NR; - Smoking: All nonsmokers or <1 cigarette/wk (part of exclusion criteria); - Diet quality: No summary metric; data on mean dietary intake available in Table 2; - TEI: Kcal/day, mean (SD): 1666 (375); Study beverage intake at baseline: 8ounce servings/day, mean (SD); Citrus juice: 0.7 (1.2); Fruit juice excluding citrus juice: 0.5 (0.8); Excluded: <18y at time of delivery; preterm or multiple birth; >1mo postpartum; no intention to breastfeed for ≥3mo postpartum, taking medications or had any medical conditions that could affect metabolism, nutritional status, or physical or mental health; current use of tobacco (i.e., >1 cigarette/wk) or other recreational drugs; clinical diagnosis of fetal abnormalities; dietary data unavailable at 1- and 6-mo postpartum (n=114); dietary sugar variables (i.e., sucrose, mannitol, soft drinks, sweets) >2 SD above mean (n=4); weight loss >11 SD above the mean (n=1) | Exposure: citrus juice; fruit juice excluding citrus juice; 8oz svg/d (236.6 mL/d); Other exposures: SSB; Comparator: Different intake of 100% juice, continuous (half a serving per day); Assessment methods and timing:; Two nonconsecutive 24-h dietary recalls (unclear if validated) conducted on 1 weekday and 1 weekend day using the multipass method. Data at all 4 time points were averaged to represent mean dietary intake.; 1 and 6 months postpartum; Outcomes and assessment methods:; Weight: valid measure by study staff.; 1 and 6 mo postpartum | Postpartum weight change from 1 to 6 mo per half 8-ounce svg/d increase in 100% juice consumption, kg, β (95% CI), multiple linear regression; Citrus juice: 0.03 (−0.32, 0.39), p=0.85; Fruit juice excluding citrus juice: −0.47 (1.02, 0.07), p=0.09 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline; - Other: Maternal height; change in breastfeeding; Limitations:; - Did not account for key confounders: socioeconomic position, physical activity, diet quality, smoking, parity; - Start of follow-up and exposure do not coincide; High missing data; No preregistered data analysis plan; Funding:; NIDDK; Gerber Foundation; National; Institute of Environmental Health Sciences

a Abbreviations: β: beta coefficient; BMI: body mass index; CI: confidence interval; d: day(s); h: hour(s); kg: kilograms; mL: milliliters; mo: month(s); NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NR: not reported; PCS: prospective cohort study; SD: standard deviation; SSB: sugar-sweetened beverages; svg: serving; TEI: total energy intake; y: year(s)

Table 20 Risk of bias for observational study examining 100% juice consumption in individuals during postpartum and postpartum weight change^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Alderete, 2020^52^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. )