# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 5 systematic reviews assessing the relationship between beverage consumption (100% juice, dairy milk and milk alternatives^†^; beverage patterns^‡^; low- and no-calorie sweetened beverages^§^; and sugar-sweetened beverages^**^) and growth, body composition, and risk of obesity. The literature search (Appendix 4) yielded 36,223 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 33,121 titles, 2,552 abstracts, and 463 full-text articles. Reasons for full-text exclusion are in Appendix 5. Two additional articles with data on 100% juice and relevant outcomes were identified from the manual search, and 4 articles were identified as part of the complementary feeding and growth, body composition, and risk of obesity systematic review.^††^ In total, the body of evidence examining 100% juice included 52 articles:

- Infants, children and adolescents: 29 articles^1–29^
- Adults and older adults: 21 articles^30–50^
- Individuals during pregnancy and postpartum: 2 articles^51,52^

† Raynor HA, Deierlein AL, Gardner CD, . Dairy Milk and Milk Alternatives and Growth, Body Composition, and Risk of Obesity: A Systematic Review U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR03

‡ Raynor HA, Deierlein AL, Gardner CD, . Beverage Patterns and Growth, Body Composition, and Risk of Obesity: A Systematic Review U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR02

§ Raynor HA, Deierlein AL, Gardner CD, . Low- and No-Calorie Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR04

** Deierlein AL, Raynor HA, Andres A, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR23

†† Fisher JO, Abrams SA, Andres A, . Complementary Feeding and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR18

Figure 2 Literature search and screen flowchart

The literature searches in PubMed, Embase, Cochrane, and CINAHL, retrieved 36,223 records after removing duplicates. 167 were included from existing reviews. 38 were found with manual search methods. 33,121 titles, 2,552 abstracts, and 463 full-texts were excluded. 292 articles were included across the systematic reviews examining beverage consumption in the systematic review.

## Infants, children, and adolescents

### Description of the evidence

The body of evidence examining the relationship between 100% juice consumption and growth, body composition, and risk of obesity in infants and young children (up to 24 months), children, and adolescents included 29 articles, which are summarized in Table 11. Conclusion statements and grades are detailed in Table 6 and risk of bias assessments are found in Table 12 and Table 13. As noted above, details from the 4 articles on infants and young children up to age 24 months are provided below in the context of the overall review of evidence from infancy through adolescence. A description and synthesis of the evidence on 100% juice consumption and growth, body composition, and risk of obesity specific to infants and young children is provided in another systematic review conducted by the Committee on complementary feeding.^*^

* Fisher JO, Abrams SA, Andres A, . Complementary Feeding and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR18

#### Population

Of the 29 articles in infants, young children, children, and adolescents, 1 article was from a randomized controlled trial (RCT) and 28 articles were from prospective cohort studies (PCS). Most studies were conducted in the United States; however, there were also studies from the United Kingdom,^3,8,14^ Australia,^28^ Canada,^9^ Denmark,^29^ and Germany.^16^

The RCT^13^ was conducted in the U.S. and enrolled 136 adolescent middle school students (mean age: 13 years) in a 6-month study; 86% of participants were from minority racial and/or ethnic groups and mean BMI was approximately at the 85^th^ percentile. Socioeconomic position (SEP) was not reported.

The 28 articles from PCS were from 24 independent cohorts; 3 articles were a secondary analysis of data from an RCT.^7,18,28^ Sample sizes ranged from N=21^18^ to N=15,418 participants,^12^ with 21 articles involving sample sizes less than 1000 participants. Lengths of follow-up ranged from 8 weeks^18^ to 10 years.^26^ Most articles included children ages 2 to 12 years at baseline; 10 articles included children with a mean baseline age of 2-5 years and 11 were conducted in children 6-12 years at baseline. Four articles were identified in infants and young children, up to 24 months,^1–4^ and 3 articles included study populations with a mean baseline age greater than 12 years.^20,21,25^

Six of the 28 PCS articles did not report race and/or ethnicity data, and 12 articles did not report information on SEP. Of those that did provide information on race and/or ethnicity, 15 articles were from studies in predominantly White populations, 6 articles reported that >50% of participants were from racial and/or ethnic minority groups, and 1 article reported that most participants had at least one parent from Australia or New Zealand. Nine articles were from studies conducted in middle- to higher-SEP populations, while 7 articles were from studies conducted in lower-SEP populations.

#### Intervention/exposure and comparator

The intervention or exposure of interest for this systematic review question was 100% juice, which included 100% fruit juice, 100% vegetable juice, or a combination of the two, but did not include juice drinks with added sugar. Eligible comparators were consumption of a different amount of 100% juice (including no consumption and versions diluted with water), 100% juice vs. water, or 100% juice vs. solid (i.e., a whole fruit or vegetable).

The RCT^13^ enrolled participants into a 6-month resistance training intervention in which they were randomized to consume either 100% fruit juice, water (control), or milk (analyses not included in this review). Participants in the juice group chose between apple, orange, or grape juice and consumed 4, 6-ounce servings per day; the control group consumed an equal amount of water.

All PCS articles examined varying levels of 100% juice intake as their exposure and comparator of interest. Nine articles assessed juice intake through dietary recalls, while 10 articles used food frequency questionnaires, 6 articles collected exposure data via parent survey or interview, and 3 articles used weighed food and beverage records. Seventeen articles compared juice intake continuously and 11 articles categorically compared different intake levels of juice (e.g., tertiles of juice servings per week). The units used to measure juice intake varied across articles (e.g., servings, ounces, grams, cups, kilocalories), as did the time scale for consumption (e.g., intake per day or week).

#### Outcomes

The RCT^13^ assessed the effect of 100% juice compared with water on growth, body composition and risk of obesity outcomes, including BMI percentile, fat mass, fat-free mass, percent fat, waist circumference, and weight. Outcomes were described by group in the full sample as well as by sex.

In the PCS, 16 articles reported growth outcomes (e.g., BMI z-score, height, weight),^1–3,6–8,10,15–17,19,21–23,28,29^ 7 articles reported body composition outcomes (e.g., percent body fat, waist circumference),^7,11,14–16,28,29^ and 14 articles included risk of obesity outcomes (e.g., BMI change, risk of overweight).^5,9,12,18–21^ Shefferly, 2016}^4,23–27^ Seven articles included outcomes based on self- or parent-reported height and/or weight, which was used to calculate BMI^5,9,10,20,21,25^ or weight-for-age z-score.^2^ All other articles reported outcomes measured by study personnel.

#### Studies included in meta-analyses

Overall, 16 articles from 14 PCS provided usable data for meta-analyses.^3,7,8,10,12,16,17,19–25,28,29^ Because only one RCT^13^ met the inclusion criteria, it was not included in the meta-analysis. Articles were excluded from the meta-analysis for the following reasons: analysts were unable to estimate an effect size,^6,15,18,26^ the reported exposure or outcome was not analyzed due to too few studies,^1,2,4,5,9,11,14,27^ or the outcome did not meet the inclusion criteria for meta-analysis.^17^

The population characteristics of the articles included in the meta-analyses were similar to the full body of evidence—including countries where studies were conducted, racial and/or ethnic and socioeconomic diversity of included samples, mean duration of follow-up, and analytic sample sizes.

Contribution of the studies in infants and young children, up to age 24 months, at the time of exposure assessment, to the meta-analyses were relatively minimal due to the small number of studies and/or lack of data compatibility. Ultimately, 1 article^3^ in this population was included for meta-analysis. Among studies that assessed the exposure in children age 2 years or older, the mean age was similar to that among all studies included in the systematic review. Compared to the full systematic review, the meta-analyses included relatively fewer studies of children with any weight status at baseline,^7,10,12,19,21^ ^22,25,28,29^ as opposed to studies that were limited to children with overweight or obesity, or studies that were limited to children without those conditions.

All articles included in meta-analysis examined 100% juice intake at baseline; there were not enough articles examining change in 100% juice intake to conduct a meta-analysis. All articles reported measures of BMI zscore,^3,7,12,16,17,23,24^ change in BMI z-score,^10,19–22,25,28,29^ or change in weight.^8,19,21^

### Synthesis of the evidence

Articles in infants, children and adolescent populations were synthesized together. Since energy intake is an important covariate when interpreting studies on the relationship between 100% juice consumption and growth, body composition, and risk of obesity, articles were organized by whether or not they adjusted for TEI. Both approaches were considered within the evidence synthesis. Sixteen articles adjusted for TEI, with 5 of these presenting both adjusted and unadjusted results.^5,10,19,28,29^ With the exception of 1 article,^10^ adjusting for TEI did not change the statistical significance of the findings.

Most articles (19 of 29) reported only null findings in the association between 100% juice and growth, body composition and risk of obesity outcomes. Among articles with statistically significant findings, there were more inverse associations than direct associations, though many statistically significant associations were in studies that did not adjust for TEI. In several articles, findings were not consistent when stratified by sex or by racial and/or ethnic group.

#### Randomized controlled trial

The RCT^13^ found no differences between the 100% juice group and the water control in any outcomes (BMI percentile, fat mass, fat-free mass, percent fat, waist circumference, and weight) after the 6-month intervention in the full study population. Results stratified by sex were presented, but due to small sample sizes the study was underpowered to detect any sex-specific findings.

#### Prospective cohort studies

##### Growth outcomes

Sixteen PCS articles reported a range of outcomes related to growth, most commonly change in BMI z-score,^6–8,10,15–17,22,28,29^ and also BMI z-score at follow-up,^3^ change in BMI percentile,^21^ weight^19,21,23^ or weight-for-age zscore,^2,22^ and change in height^21,23^ or height-for-age z-score.^21,22^

Eight of the 11 articles with BMI z-score outcomes did not find a relationship between 100% juice intake.^3,6–8,15,17,28,29^ These articles covered a range of ages, but mainly had small sample sizes. Among the articles that reported statistically significant results, Libuda et al^16^ found that greater increase in 100% juice intake was related to greater increase in BMI standard deviation score over five years, but only in girls (mean age at baseline: 12 years). Similarly, in another much larger study (N=14,918) with a mean baseline age of 12 years, fruit juice intake was associated with greater change in BMI z-score (based on self-reported height and weight) in girls over 3 years of follow-up; this relationship only reached statistical significance after adjusting for TEI.^10^ In a much younger population, Shefferly et al^22^ found a greater change in BMI z-score from age 2 years to 4 years for children drinking ≥1 serving of juice per day, compared with those consuming less than 1 serving per day; this relationship was no longer significant when follow-up was measured from age 4 to 5 years. The one paper with change in BMI percentile outcomes did not find an association with 100% juice intake.^21^

Only 1 of the 5 articles with weight or weight z-score outcomes found an association with juice intake.^2^ Gaffney et al^2^ found that a higher intake frequency of 100% juice (greater than 1 feeding of juice per 2 days versus none) from 6 to 12 months was significantly associated with higher weight-for-age z-score at 12 months. Three studies included height-related outcomes,^21–23^ two of which found an association with juice intake. However, the direction of the relationship was inconsistent, as were the results stratified by sex. Sakaki et al^21^ found that higher orange juice intake was associated with greater change in height-for-age z-score in girls after 2 years of follow-up (calculated using self-reported height), but not in boys. In the same study, increasing juice intake was nonlinearly associated with greater change in self-reported height, but only in boys. Shefferly et al^22^ found that increasing juice consumption from age 2 to age 4 years was inversely associated with change in height-for-age z-score; this relationship was no longer significant when change was measured from 4 to 5 years of age.

##### Body composition outcomes

None of the 7 PCS articles reporting body composition outcomes found an association with 100% juice intake.^7,11,14–16,28,29^ Sample sizes were relatively small for cohort studies, ranging from N=49 to N=682, with all but 1 having less than 400 participants. The most commonly reported outcome was percent body fat^7,11,16,28^; only 2 articles assessed waist circumference^15,29^ and there was 1 article each for fat mass,^14^ fat mass index quintile,^14^ and sum of skinfolds.^29^

##### Risk of obesity outcomes

Fourteen PCS articles reported outcomes related to risk of obesity. The most commonly assessed outcome was change in BMI, which was included in 8 articles.^5,19–21,23–26^ Only 1 of these found an association between juice intake and change in BMI: Sakaki et al^20^ found that higher consumption of total fruit juice and orange juice was associated with greater BMI reduction over 2 years in girls, but not in boys. There was no association between non-orange fruit juices and BMI change in girls. However, BMI measurements in this study were not age- or sex-specific.

Two articles assessed BMI after 2 years^12^ or across 5 years of follow-up.^9^ Both found a relationship between 100% juice intake and BMI; however, results were not consistent across racial and/or ethnic groups or when stratified by sex. Guerrero et al^12^ found that higher 100% juice consumption was significantly associated with lower age- and sex-specific BMI from age 4-6 years but only in White participants; results were not significant for Black, Asian, or Hispanic participants. Dubois et al^9^ analyzed adolescent monozygotic boy and girl twin pairs and found that higher juice intake was associated with lower BMI over 5 years in the overall study sample (N=304), but results were not significant in any sub-analyses, including stratifications by sex and BMI concordance.

Three articles examined risk of obesity and/or obesity in children ages 5 and under.^4,22,27^ Vandyousefi et al^4^ found that consumption of any 100% fruit juice during the first year of life was associated with higher odds of obesity at 2 to 5 years when compared to no consumption of 100% fruit juice. In a cohort of over 10,000 participants, Welsh et al^27^ found an increased risk of overweight in those with higher juice intake after 1 year of follow-up, but only if participants had overweight at baseline (mean baseline age: 3 years). Results were nonlinear: while there was a relationship for those consuming 2 to < 3 servings of juice per day, there was no association with the highest tertile of juice consumption (≥3 servings per day). Shefferly et al^22^ found an increased risk of overweight, but not obesity, at age 4 in those consuming ≥1 serving of juice per day compared to those consuming < 1 serving per day (intake assessed at age 2). There was no association with juice intake and risk for overweight or obesity from age 4 to 5 years, by juice intake at age 4. Only 1 study looked at the relationship between 100% juice intake and weight gain; no association was found, but study duration was short (8 weeks) and sample size was very small (N=21).^18^

#### Meta-analysis

Six observations (i.e., effect sizes) from five cohorts^7,16,17,23,24^ were included in meta-analyses of 3,564 children to examine the relationship between 100% juice intake at baseline, measured continuously, and BMI z-score at follow-up (Table 5, Figure 3, Figure A 1 through Figure A 11). The pooled effect estimate was approximately zero, and the 95% CI for the mean included zero for all analyses. Heterogeneity, as measured by tau^2^, I^2^, and 95% PI, was very low. Results were consistent across the main and subgroup analyses. The relationship did not differ by TEI adjustment or by weight status at baseline. The results did not vary by age, although there were no studies that examined this relationship among infants and young children up to age 24 months at baseline.

Figure 3 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/d), and BMI z-score at follow-up.*

* Risk of bias due to A: confounding; B: selection of participants into the study; C: measurement of the exposure; D: post-exposure interventions; E: missing data; F: measurement of the outcome; G: selection of the reported result; +: Low risk of bias; ?: Some concerns of risk of bias; -: High risk of bias; BMI: body mass index; CI: confidence interval; RE: random effects; CI: confidence interval; d: day; oz: ounce; RE: random effects; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and BMIZ at follow-up in children. Overall, there was not a statistically significant difference in BMIZ by 100% juice intake: 0.00 (95% CI: −0.01, 0.01). Risk of bias domains are also reported (see Table 13 for additional information).

Results were similar for the remaining analyses of the relationship between 100% juice intake at baseline and BMI z-score, change in BMI z-score, and change in weight, which are summarized in Table 5, and in Appendix 6. Pooled estimates were consistently near zero, with low heterogeneity in both the main analyses and subgroup analyses. When the I^2^ measure was high, the 95% CI of the I^2^ was wide, suggesting uncertainty in the I^2^ estimate. Some subgroup analyses were difficult to interpret due to the small number of studies, particularly when intake was measured categorically. Additionally, there were not enough studies to complete quantitative analyses of the risk of reporting bias (i.e., funnel plots or tests of funnel plot asymmetry).

Due to the limited number of results in each exposure-outcome group, as well as the consistency in findings across analyses, dose-response analyses and other planned meta-regressions were not conducted.

Table 5 Summary of meta-analyses

Exposure and outcome | Summary statistics | Sample size
Intake at baseline (continuous, per 8 oz/d) and BMI z-score at followup | Main analysis; Pooled slope: 0.00 (−0.01, 0.01), p=0.55, tau^2^=0.00, I^2^: 0% (0, 99), 95% PI: −0.01, 0.01 | 6 observations from 5 articles,^7,16,17,23,24^ including 3,564 children
Intake at baseline (categorical, any level of intake vs none/rarely) and BMI z-score at follow-up | Main analysis; Pooled slope: −0.06 (−0.12, −0.00), p=0.04, tau^2^=0.00, I^2^: 0% (0, 0), 95% PI: −0.12, −0.00 | 2 observations from 2 articles,^3,12^ including 16,140 children
Intake at baseline (continuous, per 8 oz/d) and change in BMI zscore | Main analysis; Pooled slope: −0.00 (−0.00, 0.00), p=0.67, tau^2^=0.00, I^2^: 49% (0, 100), 95% PI: −0.01, 0.00 | 7 observations from 5 articles,^10,19,20,28,29^ including 24,952 children
Intake at baseline (categorical, <1 vs ≥1 svg/d) and change in BMI z-score | Main analysis; Pooled slope: −0.02 (−0.06, 0.01), p=0.25, tau^2^=0.00, I^2^: 0% (0, 83), 95% PI: −0.06, 0.01 | 4 observations from 3 articles,^21,22,25^ including 15,845 children
Intake at baseline (continuous, per 8 oz/d) and change in weight | Main analysis; Pooled slope: −0.00 (−0.04, 0.04), p=0.98, tau^2^=0.00, I^2^: 18% (0, 70), 95% PI: −0.06, 0.06 | 4 observations from 3 articles,^8,19,21^ including 13,292 children

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed and graded a conclusion statement for the systematic review question: “What is the relationship between 100% juice consumption and growth, body composition, and risk of obesity?” based on review of the totality of evidence in infants, children, and adolescents (see Table 6).

The Committee also examined the evidence in infants and young children, up to 24 months, independent of older children and adolescents as part of the systematic review on complementary feeding and growth, body composition, and risk of obesity. For that review,^*^ the Committee did not draw a conclusion statement about the relationship between 100% juice consumption by infants and young children, up to 24 months, and outcomes related to growth, body composition, and risk of obesity due to substantial concerns with consistency and precision in the body of evidence. Because of this decision, the conclusion statement below primarily refers to children and adolescents (2 up to 19 years) due to the lack of evidence in infants and young children, up to 24 months.

* Fisher JO, Abrams SA, Andres A, . Complementary Feeding and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR18

Table 6 Conclusion statement and grade for 100% juice consumption and growth, body composition, and risk of obesity in children and adolescents

Conclusion Statement | 100% juice consumption by children and adolescents is not associated with growth, body composition and risk of obesity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 1 RCT; 28 prospective cohort studies (16 in meta-analyses)
Consistency | Few concerns with consistency in findings across studies
Precision | Some concerns due to small sample sizes
Risk of bias | Some concerns with risk of bias, primarily due to confounding and missing data
Directness | Few concerns with directness across studies
Generalizability | Some concerns with generalizability to the US population, including few studies in infants and young children

#### Assessment of the evidence

The body of evidence underlying the conclusion statement above includes articles from 1 RCT and 28 PCS (16 included in meta-analysis). The evidence was graded based on an assessment of 5 grading elements, as described below. In addition, publication bias was also a consideration; however, it was not deemed a serious concern for this body of evidence because most studies reported only nonsignificant findings while others reported significant findings or a mix of significant and nonsignificant.

##### Consistency

Most articles reported a null relationship between 100% juice intake and growth, body composition, and risk of obesity outcomes, especially those that adjusted for TEI. Results were somewhat mixed in studies that did not adjust for TEI and in the infants and young children and adolescent populations, but the majority of articles still showed no relationship. Meta-analysis results showed consistency in the direction and magnitude of findings across analyses and low heterogeneity, confirming a lack of relationship between juice consumption and both weight and BMI.

##### Precision

The RCT sample size was small (N=34 to N=38 per group) and post-hoc analyses of the primary outcomes determined that they were underpowered. Multiple observational cohorts also had smaller sample sizes (N<100), though many were in the thousands. For meta-analysis, there were few unique samples, but all analyses included a relatively large number of individuals. In the observational studies, the units used to measure juice intake varied, as did the time scale for consumption, which made comparison of effect sizes and confidence intervals difficult.

##### Risk of bias

Risk of bias assessments for each article are detailed in Table 12 (RCT) and Table 13 (PCS). None of the 28 PCS articles accounted for all key confounders. There were also substantial concerns due to missing data (large study cohorts with high attrition or exclusion) and selection of the reported results, as none of the articles had a predefined data analysis plan.

##### Directness

The RCT was not designed to directly assess this research question and many of the PCS had broader research objectives; however, articles included in this review still provided adequate data for directly assessing the relationship of interest.

##### Generalizability

Most included studies were conducted within the United States. Age ranges across childhood were well represented, although there were relatively few studies in adolescents. This body of evidence had greater diversity in race and/or ethnicity and SEP than other beverage types included for systematic review. Even so, the vast majority of articles reporting race and/or ethnicity information were from studies in predominantly White populations. Nearly half of the articles did not provide SEP information, but of those that did, there was a near-even split between those conducted in middle- to higher-SEP populations and those in lower-SEP populations. One substantial concern with generalizability was the small number of studies in infants and young children, limiting the ability to draw conclusions about the relationship of 100% juice to growth, body composition, or risk of obesity outcomes in this population.

## Adults and older adults

### Description of the evidence

This review included 21 articles examining 100% juice consumption in adults and body composition and risk of obesity. Four articles were parallel RCTs^30,40,48,49^ and 17 articles were PCS^31–39,41–47,50^; meta-analysis was not conducted in this population. The following sections summarize the body of evidence used to answer this systematic review question, and the overall conclusion statements and grades are detailed in Table 7 and Table 8. Evidence for 100% juice consumption in adults and body composition and risk of obesity is summarized in Table 14, and risk of bias assessments are detailed in Table 15 (RCT) and Table 16 (PCS).

#### Population

Studies were conducted in populations from the following countries: Brazil,^30,50^ Canada,^36^ Denmark,^39^ Iran,^41^ Italy,^33^ Spain,^37,38,42^, and the U.S.^31,32,34,35,40,43–45,47–49^ One study was conducted in populations from multiple countries in Europe.^46^

The 4 RCT articles had a mean baseline age ranging from approximately 25 to 50 years. One trial enrolled only females,^30^ 2 trials had >70% female enrollment,^48,49^ and one trial enrolled men and women but did not report the percentage of each.^40^ Analytic sample sizes ranged from N=26 to N=76. Three trials^40,48,49^ had inclusion criteria for BMI ≥25 kg/m^2^ or ≥30 kg/m^2^ and 2 had inclusion criteria related to low or no habitual juice consumption at baseline.^30,40^ Two trials did not report data on race and/or ethnicity,^30,40^ one trial enrolled Black and White adults,^49^ and one trial enrolled an ethnically diverse sample.^48^

The 17 PCS articles were from 13 independent cohorts with a mean baseline age ranging from approximately 25 to 67 years. Four of these articles were from studies conducted in females only.^31,32,45,47^ Sample sizes ranged from N=248 to N=52,987. Nine articles did not report data on race and/or ethnicity,^32,33,36–39,41,46,47^ 5 articles were in primarily White participants,^31,42–45^ and 3 articles were from ethnically diverse cohorts.^34,35,50^ Eight articles did not report data on SEP,^32,33,35–37,39,46,47^ 3 articles were from primarily well-educated samples,^43,45^ and 6 articles were diverse in terms of participant education level.^31,34,38,41,42,50^

#### Intervention/exposure and comparator

The trials included a variety of interventions and were inconsistent in the type and amount of juice consumed. Aptekman et al^30^ compared 500 milliliters (mL)/day of orange juice to a usual diet control. Hollis et al^40^ compared 480 mL/day of grape juice to a usual diet control. Silver et al^49^ compared 127 grams of grapefruit juice before breakfast, lunch, and dinner to water and solid grapefruit. Shenoy et al^48^ compared different amounts (none, 8-ounce, 16-ounce) of low-sodium vegetable juice. Study durations for all interventions were 12 weeks^40,48,49^ or 3 months.^30^

Most observational studies examined 100% fruit juice as the exposure of interest. Four articles examined a combination of 100% fruit and vegetable juice.^32,34,38,39^ The length of follow-up ranged from 2 to 20 years. All but 2 articles^34,36^ measured juice intake with food frequency questionnaires. About half of the articles examined juice intake as a continuous variable (e.g., servings per day, kilocalories per day) and several articles examined juice intake as a categorical variable (e.g., tertiles); 2 articles examined juice intake continuously and categorically.^35,38^

#### Outcome

In adults, outcomes included measures of body composition and risk of obesity. The most commonly reported outcomes were weight (14 articles) and waist circumference (9 articles), with most studies using measures obtained from trained study staff. Seven observational studies used self-reported measures of weight at baseline and/or follow-up.^32,39,43–47^

### Synthesis of the evidence

Three of the 21 articles were in participants with a mean age ≥60 years^33,37,42^; therefore, the evidence in adults and older adults was synthesized together. Since energy intake is an important covariate when interpreting studies on the relationship between 100% juice consumption and body composition and risk of obesity, articles were organized by whether or not they adjusted for TEI. Both approaches were considered within the evidence synthesis. In general, most studies found no statistically significant association between 100% juice consumption and outcomes related to body composition and risk of obesity.

#### Randomized controlled trials

Shenoy et al^48^ reported favorable weight outcomes after 12 weeks among 100% vegetable juice consumers compared to the control group. The other 3 trials examined 100% fruit juice consumption^30,40,49^; all of these had null findings related to body composition or risk of obesity.

#### Prospective cohort studies

Eight articles from 7 PCS reported body composition outcomes.^35–39,42,46,50^ All studies found no association with 100% juice intake and waist circumference. Drapeau et al^36^ also examined body fat percentage and sum of skinfolds but found no association with juice intake. All but 1 article^36^ accounted for TEI.

Eleven articles from PCS reported measures related to risk of obesity.^31–34,36,41–45,47^ Of these, 7 articles found that increased consumption of 100% juice was related to greater weight gain.^31,32,41,43–45,47^ Four articles did not account for TEI.^36,43,44,^47

### Conclusion statements and grades

The Committee developed and graded conclusion statements for the systematic review question: “What is the relationship between 100% juice consumption and growth, body composition, and risk of obesity?” based on their review of evidence in adults (see Table 7 and Table 8).

Table 7 Conclusion statement and grade for 100% juice consumption and body composition in adults

Conclusion Statement | 100% juice consumption by adults and older adults is not associated with body composition. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 3 RCT; 8 articles from prospective cohort studies
Consistency | Few concerns with consistency across the body of evidence
Precision | Substantial concerns with precision due to the small number of studies and varying metrics across them
Risk of bias | Some concerns with risk of bias, primarily due to confounding and missing data
Directness | Some concerns with directness due to variation in the type of juice measured
Generalizability | Substantial concerns with generalizability to the US population due to weight status in the trials and limited racial and/or ethnic and socioeconomic diversity in the cohort studies

#### Assessment of the evidence

The body of evidence underlying the conclusion statement includes 3 articles from RCT and 8 articles from 7 independent cohorts. The evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also a consideration but was not a serious concern for this body of evidence because publications included both large and small studies, and studies in this body of evidence were consistent in reporting non-significant findings.

##### Consistency

The RCT data were consistent, with all trials finding no effect of 100% juice consumption in adults and body composition. The observational data were also consistent, with all studies finding no association between 100% juice consumption in adults and body composition.

##### Precision

There was a small number of trials with sample sizes ranging from N=26 to N=76 participants. Trials were inconsistent in the type of juice assessed and accounting for TEI. Observational studies used varying metrics (e.g., serving size, continuous/categorical exposures) making comparison of effect sizes and confidence intervals difficult.

##### Risk of bias

Trials did not report adequate information on their methods for randomization or concealment and did not provide a preregistered data analysis plan. Most observational studies did not account for at least one key confounder and had risk of bias related to missing data.

##### Directness

Although the trials were designed to directly answer the research question, the studies examined different juice types. The observational studies had no notable issues with directness but tended to have broader research objectives.

##### Generalizability

Trials were limited to individuals with overweight or obesity at baseline and were targeting weight loss. Only 2 trials reported data on race and/or ethnicity or SEP, limiting the ability to assess generalizability. Many observational studies enrolled only women or were from samples of predominantly White adults, limiting the generalizability to other groups.

Table 8 Conclusion statement and grade for 100% juice consumption and risk of obesity in adults

Conclusion Statement | 100% juice consumption by adults and older adults may not be associated with weight gain. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 4 RCT; 11 prospective cohort studies
Consistency | Substantial concerns with consistency in the direction of findings
Precision | Substantial concerns due to varying metrics across studies
Risk of bias | Some concerns with risk of bias, primarily due to confounding and missing data
Directness | Some concerns with directness due to variation in the type of juice measured
Generalizability | Substantial concerns with generalizability to the US population due to weight status in the trials and limited racial and/or ethnic and socioeconomic diversity in the cohort studies

#### Assessment of the evidence

The body of evidence underlying the conclusion statement includes 4 RCT and 11 PCS. The evidence was graded based on an assessment of 5 grading elements, as described below. Publication bias was also a consideration but was not a serious concern for this body of evidence because publications included both large and small studies, and multiple studies only reported non-significant findings.

##### Consistency

The RCT data were consistent, with most trials finding no association between 100% juice consumption in adults and weight. The observational data were less consistent for weight.

##### Precision

There was a small number of trials, all with short duration (12 weeks to 3 months) and small sample sizes. Trials were inconsistent in the type of juice assessed (one examined vegetable juice) and accounting for TEI. Observational studies used varying metrics (e.g., serving size, continuous/categorical exposures) making comparison of effect sizes and confidence intervals difficult.

##### Risk of bias

Trials did not report adequate information on their methods for randomization or concealment and did not provide a preregistered data analysis plan. Most observational studies did not account for at least one key confounder and had risk of bias related to missing data.

##### Directness

Although the trials were designed to directly answer the research question, the studies examined different juice types. The observational studies had no notable issues with directness but tended to have broader research objectives.

##### Generalizability

Trials were limited to individuals with overweight or obesity at baseline and were targeting weight loss. Observational studies that reported data on race and/or ethnicity were in predominantly White participants with middle- to higher SEP. One study enrolled participants with lower SEP.

## Individuals during pregnancy and postpartum

### Description of the evidence

This review included 1 article examining 100% juice consumption during pregnancy and gestational weight gain^51^ and 1 article examining 100% juice consumption during postpartum and postpartum weight change.^52^ The overall conclusion statements and grades answering the systematic review question are detailed in Table 9 and Table 10. Evidence for 100% juice consumption during pregnancy and gestational weight gain is summarized in Table 17, and evidence for 100% juice consumption during postpartum and postpartum weight change is summarized in Table 19.

Both articles were prospective cohort studies conducted in the U.S. in predominantly Hispanic women with a mean baseline age of 27 to 29 years. Guilloty et al^51^ examined the relationship between dichotomous juice intake (<1/day vs. ≥1/day) measured from a FFQ between 20- to 28-week gestation and adequacy of gestational weight gain based on Institute of Medicine (IOM) 2009 guidelines. Alderete et al^52^ examined the relationship between change in juice intake (per half 8-ounce serving per day) measured using two 24-hour diet recalls and researcher-measured postpartum weight change from 1- to 6-months postpartum.

### Synthesis of the evidence

Guilloty et al^51^ found no relationship between 100% juice intake during pregnancy and gestational weight gain. Alderete et al^52^ found no relationship between 100% juice intake during postpartum and postpartum weight change. Both studies did not account for more than 1 key confounder and did not have a preregistered data analysis plan (see risk of bias assessments in Table 18 and Table 20).

### Conclusion statements and grades

The Committee developed conclusion statements for the systematic review question: “What is the relationship between 100% juice consumption and growth, body composition, and risk of obesity?” based on their review of evidence in individuals during pregnancy and postpartum. Conclusion statements could not be drawn for these populations due to a lack of evidence.

Table 9 Conclusion statement and grade for 100% juice consumption and gestational weight gain

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between 100% juice consumption during pregnancy and adequacy of gestational weight gain because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article
Rationale | There was only one eligible article examining 100% juice consumption and gestational weight gain.

Table 10 Conclusion statement and grade for 100% juice consumption and postpartum weight change

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between 100% juice consumption during postpartum and postpartum weight change because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article
Rationale | There was only one eligible article examining 100% juice consumption and postpartum weight change.