# Appendix 6 Meta-analysis supplementary materials

Table A 14 Data transformations and assumptions for meta-analyses^*^ * Abbreviations: β: regression coefficient; BMI: body mass index; CI: confidence interval; d: day; dBMI z-score: change in body mass index z-score; kcal: kilocalorie; MJ: megajoule; mo: month; NR: not reported; NS: non-significant; OWO: overweight/obesity; oz: ounce; SE: standard error; svg: serving; TEI: total energy intake; vs: versus; y: year; Z: z-value

Reference Observation | Extracted Data | Transformation and Assumptions | Transformed Effect Estimates
Carlson, 2012^7^; BMI z-score | 2y change in BMI z-score per 8 oz/d increase in juice; β (95% CI); -0.04 (−0.21, 0.13), P=0.631 | Converted 95% CI to SE | β (SE); -0.04 (0.087)
Field, 2003^10^; dBMI z-score, females, TEI adjusted | Annual change in BMI z-score per svg/d juice; β (95% CI); 0.003 (0.001, 0.005) | Converted 95% CI to SE; Serving size NR, assumed 8 oz/svg | β (SE); 0.003 (0.001)
Field, 2003^10^; dBMI z-score, males, TEI adjusted | Annual change in BMI z-score per svg/d juice; β (95% CI); 0.002 (0.000, 0.005) | Converted 95% CI to SE; Serving size NR, assumed 8 oz/svg | β (SE); 0.0020 (0.0013)
Field, 2003^10^; dBMI z-score, females, TEI unadjusted | Annual change in BMI z-score per svg/d juice; β (95% CI); -0.000 (−0.002, 0.001) | Converted 95% CI to SE; Serving size NR, assumed 8 oz/svg | β (SE); 0.0000 (0.0008)
Field, 2003^10^; dBMI z-score, males, TEI unadjusted | Annual change in BMI z-score per svg/d juice; β (95% CI); 0.000 (−0.002, 0.002) | Converted 95% CI to SE; Serving size NR, assumed 8 oz/svg | β (SE); 0.0000 (0.0010)
Guerrero, 2016^12^; BMI z-score | BMI for any juice vs. none; β (SE); -0.101 (0.053), P=NS | BMI was converted to BMI z-score using the LMS method.^*^; * Growth Charts – Percentile Data Files with LMS Values (https://www.cdc.gov/growthcharts/percentile_data_files.htm); LMS values at 60.5 months were used and the average of boys and girls were calculated for the β and SE. | β (SE); -0.06 (0.032)
Libuda, 2008^16^; BMI z-score, males | BMI z-score per MJ/d juice*time; β; 0.033, P=0.310 | Estimated SE from p-value and β using SE=β/Z. Coefficients were converted from MJ (~240 kcal) to 8 oz servings by dividing estimates by 2 (assumed juice averages ~15.3 kcal/oz)^†^; † FoodData Central (https://fdc.nal.usda.gov/) | β (SE); 0.02 (0.033)
Libuda, 2008^16^; BMI z-score, females | BMI z-score per MJ/d juice*time; β; -0.046, P=0.161 | Estimated SE from p-value and β using SE=β/Z. Coefficients were converted from MJ (~240 kcal) to 8 oz servings by dividing estimates by 2 (assumed juice averages ~15.3 kcal/oz)^†^ | β (SE); -0.02 (0.023)
Mahoney, 2018^3^; BMI z-score | BMI z-score for any juice vs. none; β (95% CI); -0.05 (−0.20, 0.10), P=0.53 | Converted 95% CI to SE | β (SE); -0.05 (0.077)
Marshall, 2019^17^; BMI z-score | BMI z-score per 8 oz/d juice; β (95% CI); 0.044 (−0.038, 0.125) | Converted 95% CI to SE | β (SE); 0.04 (0.042)
Newby, 2004^19^; dBMI z-score, TEI adjusted | Change in BMI per oz/d juice; β (SE); 0.01 (0.00), P=0.20 | Estimated a non-zero SE from p-value and β using SE=β/Z; BMI was converted to BMI z-score using the LMS method.^*^ LMS values at 34.5 months were used and the average of boys and girls were calculated for the β and SE.; Coefficients were converted from 1 oz to 8 oz servings by multiplying estimates by 8 | β (SE); 0.0595 (0.046)
Sakaki, 2021a^21^; Change in weight, males | Change in weight (kg) per category of orange juice intake; Mean (SE); 11.7 (7.4),11.5 (7.6),11.3 (7.4), 11.1 (6.9) | Estimated kg change per 2 y per 6 oz serving/mo via regression of Table 2 data.; Coefficients were converted from to kg change per year per 8 oz/d by multiplying by 20. | β (SE); -0.358 (6.028)
Sakaki, 2021a^21^; Change in weight, females | Change in weight per 6 oz/d orange juice; Mean (SE); 6.1 (6.4), 6.1 (6.1), 6.0 (5.7), 6.0 (5.3) | Estimated kg change per 2 y per 6 oz serving/mo via regression of Table 2 data, presuming 0.5, 2, 14, and 30 servings/mo across categories.; Coefficients were converted from to kg change per year per 8 oz/d by multiplying by 20. | β (SE); -0.358 (6.028)
Sakaki, 2021b^20^; All juice, males | 2y change in BMI per 10 oz/d juice; β (SE); -0.020 (0.038), P=0.59 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); -0.055 (0.0105)
Sakaki, 2021b^20^; All juice, females | 2y change in BMI per 10 oz/d juice; β (SE); -0.102 (0.038), P=0.008 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for girls at 180.5 months were used for the β and SE.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); -0.0265 (0.0098)
Sakaki, 2021b^20^; Continuous OJ intake, males, without OWO | 2y change in BMI per 10 oz/d juice; β (SE); 0.079 (0.057), P=0.169 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE. BMI at the 50th percentile was used to approximate BMI among boys without OWO.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); 0.02 (0.02)
Sakaki, 2021b^20^; Continuous OJ intake, males, with OWO | 2y change in BMI per 10 oz/d juice; β (SE); -0.207 (0.182), P=0.255 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE. BMI at the 85th percentile was used to approximate BMI among boys with OWO.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); -0.04 (0.03)
Sakaki, 2021b^20^; Continuous OJ intake, females, without OWO | 2y change in BMI per 10 oz/d juice; β (SE); -0.105 (0.054), P=0.052 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE. BMI at the 50th percentile was used to approximate BMI among girls without OWO.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); -0.03 (0.02)
Sakaki, 2021b^20^; Continuous OJ intake, females, with OWO | 2y change in BMI per 10 oz/d juice; β (SE); -0.388 (0.206), P=0.060 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE. BMI at the 85th percentile was used to approximate BMI among girls with OWO.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); -0.06 (0.03)
Sakaki, 2021b^20^; Continuous other juice intake, males, without OWO | 2y change in BMI per 10 oz/d juice; β (SE); -0.073 (0.063), P=0.247 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE. BMI at the 50th percentile was used to approximate BMI among boys without OWO.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); -0.02 (0.02)
Sakaki, 2021b^20^; Continuous other juice intake, males, with OWO | 2y change in BMI per 10 oz/d juice; β (SE); 0.019 (0.199), P=0.924 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE. BMI at the 85th percentile was used to approximate BMI among boys with OWO.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); 0.00 (0.03)
Sakaki, 2021b^20^; Continuous other juice intake, females, without OWO | 2y change in BMI per 10 oz/d juice; β (SE); -0.047 (0.059), P=0.420 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE. BMI at the 50th percentile was used to approximate BMI among girls without OWO.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); -0.01 (0.02)
Sakaki, 2021b^20^; Continuous other juice intake, females, with OWO | 2y change in BMI per 10 oz/d juice; β (SE); -0.154 (0.215), P=0.472 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for boys at 180.5 months were used for the β and SE. BMI at the 85th percentile was used to approximate BMI among girls with OWO.; Coefficients were converted from 10 oz to 8 oz servings by multiplying estimates by 0.8 | β (SE); -0.02 (0.03)
Skinner, 2001^23^; BMI z-score | BMI per oz/d juice; β; -0.057, P=0.099 | Estimated SE from p-value and β using SE=β/Z; BMI was converted to BMI z-score using the LMS method.^*^ LMS values at 72.5 months were used and the average of boys and girls were calculated for the β and SE.; Coefficients were converted from 1 oz to 8 oz servings by multiplying estimates by 8 | β (SE); -0.306 (0.183)
Striegel-Moore, 2006^24^; BMI z-score, females | BMI per 100 g/d juice; β (SE); 0.005, (0.007), P>0.05 | BMI was converted to BMI z-score using the LMS method.^*^ LMS values for girls at 120.5 months were used for the β and SE.; Coefficients were converted from 100 g to 8 oz servings by multiplying estimates by 2.48 (juice averages 31 g/oz)^†^ | β (SE); 0.01 (.017)
Zheng, 2015a^28^; CAPS, TEI adjusted | 3.5y change in BMI z-score per 100 g/d juice; β (SE); 0.07 (0.05), P=0.12 | Coefficients were converted from 100 g to 8 oz servings by multiplying estimates by 2.48 (juice averages 31 g/oz)^†^ | β (SE); 0.1736 (0.124)
Zheng, 2015a^28^; CAPS, TEI unadjusted | 3.5y change in BMI z-score per 100 g/d juice; β (SE); 0.07 (0.05), P=0.15 | Coefficients were converted from 100 g to 8 oz servings by multiplying estimates by 2.48 (juice averages 31 g/oz)^†^ | β (SE); 0.1736 (0.124)
Zheng, 2015b^29^; EYHS, TEI adjusted | 6y change in BMI z-score per 100 g/d juice; β (SE); 0.03 (0.03), P=0.34 | Coefficients were converted from 100 g to 8 oz servings by multiplying estimates by 2.48 (juice averages 31 g/oz)^†^ | β (SE); 0.0744 (0.0744)
Zheng, 2015b^29^; EYHS, TEI adjusted | 6y change in BMI z-score per 100 g/d juice; β (SE); 0.02 (0.03), P=0.39 | Coefficients were converted from 100 g to 8 oz servings by multiplying estimates by 2.48 (juice averages 31 g/oz)^†^ | β (SE); 0.0496 (0.0744)

## 100% Juice intake at baseline and BMI z-score at follow-up

In addition to the main analysis reported above, the following subgroup analyses for 100% juice intake at baseline (measured continuously) and BMI z-score at follow-up were conducted: by total energy intake adjustment (Figure A 1) and by baseline weight status (Figure A 2). Note, subgroup analyses by age group at baseline and baseline weight status were not completed because no effects were included for infants and young children up to age 24 months.

The main analysis of 100% juice intake at baseline (measured categorically) and BMI z-score at follow-up is pictured in Figure A 3. Subgroup analyses by age group at baseline (up to age 24 months, ages 2 up to 19 years) and baseline weight status were not completed because there was only one observation in each category. Likewise, subgroup analyses by total energy intake adjustment were not conducted because no observations adjusted for total energy intake.

Figure A 1 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/d), and BMI z-score at follow-up, by total energy intake adjustment.*

* adj: adjusted; BMIZ: body mass index z-score; CI: confidence interval; RE: random effects; CI: confidence interval; d: day; oz: ounce; RE: random effects; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and BMIZ at follow-up in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In both subgroups, the 95% CI includes 0; only one study did not adjust for TEI.

Figure A 2 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/d), and BMI z-score at follow-up, by baseline weight status.^†^

^†^ BMIZ: body mass index z-score; CI: confidence interval; RE: random effects; CI: confidence interval; d: day; OWO: overweight or obesity; oz: ounce; RE: random effects; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and BMIZ at follow-up in children, by baseline weight status. The plot shows that results for participants without OWO do not significantly differ from those with any weight status. In both subgroups, the 95% CI includes 0; only one study included participants with any weight status at baseline.

Figure A 3 Meta-analysis of 100% juice intake at baseline, measured categorically (any vs rare or no intake), and BMI z-score at follow-up.^‡^

^‡^ Risk of bias due to A: confounding; B: selection of participants into the study; C: measurement of the exposure; D: post-exposure interventions; E: missing data; F: measurement of the outcome; G: selection of the reported result; +: Low risk of bias; ?: Some concerns of risk of bias; −: High risk of bias; BMIZ: body mass index z-score; CI: confidence interval; RE: random effects; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured categorically as any versus rare or no intake) and BMIZ at follow-up in children. Overall, there is an 0.09 (95% CI: 0.02, 0.16) increase in BMI with each additional 8 oz/d SSB. Overall, there was not a statistically significant difference in BMIZ by 100% juice intake: −0.06 (95% CI: −0.12, −0.00). Risk of bias domains are also reported (see Table 13 for additional information).

## 100% Juice intake at baseline and change in BMI z-score

The main analysis for 100% juice intake at baseline (measured continuously) and change in BMI z-score is depicted in Figure A 4. Subgroup analyses by adjustment for total energy intake (Figure A 5) and baseline weight status (Figure A 6) were completed, but not analyses for age group at intervention/exposure because no observations were available for infants and young children up to age 24 months.

The results for 100% juice intake at baseline (measured categorically) and change in BMI z-score are shown in Figure A 7 (main analysis) and Figure A 8 (by adjustment for total energy intake). Subgroup analyses by age group at baseline and baseline weight status were not completed because there were an insufficient number of observations in each subgroup.

Figure A 4 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/d), and change in BMI zscore.^§^

^§^ Risk of bias due to A: confounding; B: selection of participants into the study; C: measurement of the exposure; D: post-exposure interventions; E: missing data; F: measurement of the outcome; G: selection of the reported result; +: Low risk of bias; ?: Some concerns of risk of bias; −: High risk of bias; BMIZ: body mass index z-score; CI: confidence interval; d: day; oz: ounce; RE: random effects; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and change in BMIZ in children. Overall, there was not a statistically significant difference in change in BMIZ by 100% juice intake: 0.00 (95% CI: −0.01, 0.01). Risk of bias domains are also reported (see Table 13 for additional information).

Note that subgroup analyses by age group at baseline and baseline weight status were not completed because there were an insufficient number of observations.

Figure A 5 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/d), and change in BMI zscore, by total energy intake adjustment.**

** adj: adjusted; BMIZ: body mass index z-score; CI: confidence interval; d: day; oz: ounce; RE: random effects; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and change in BMIZ in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In both subgroups, the 95% CI includes 0.

Figure A 6 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/d), and change in BMI zscore, by baseline weight status.^††^

^††^ BMIZ: body mass index z-score; CI: confidence interval; d: day; ML: multilevel; OWO: overweight or obesity; oz: ounce; RE: random effects; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and change in BMIZ in children, by baseline weight status. The plot shows that results for participants without OWO or with OWO do not significantly differ from those with any weight status. In all three subgroups, the 95% CI includes 0.

Figure A 7 Meta-analysis of 100% juice intake at baseline, measured categorically (<1 versus ≥1 servings/day), and change in BMI z-score.^‡‡^

^‡‡^ Risk of bias due to A: confounding; B: selection of participants into the study; C: measurement of the exposure; D: post-exposure interventions; E: missing data; F: measurement of the outcome; G: selection of the reported result; +: Low risk of bias; ?: Some concerns of risk of bias; −: High risk of bias; BMIZ: body mass index z-score; CI: confidence interval; d: day; RE: random effects; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured categorically as <1 versus =1 serving/d) and change in BMIZ in children. Overall, there was not a statistically significant difference in change in BMIZ by 100% juice intake: −0.02 (95% CI: −0.06, 0.01). Risk of bias domains are also reported (see Table 13 for additional information).

Figure A 8 Meta-analysis of 100% juice intake at baseline, measured categorically (<1 versus ≥1 servings/day), and change in BMI z-score, by total energy intake adjustment.^§§^

^§§^ adj: adjusted; BMIZ: body mass index z-score; CI: confidence interval; d: day; RE: random effects; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured categorically as <1 versus =1 serving/d) and change in BMIZ in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In the TEI-unadjusted subgroup, the 95% CI includes 0; only one study adjusted for TEI.

## 100% Juice intake at baseline and change in weight

Meta-analyses examining the relationship between 100% juice intake at baseline and change in weight were conducted (Figure A 9), including subgroup analyses by total energy intake adjustment (Figure A 10) and baseline weight status (Figure A 11). A subgroup analysis was not completed for age group at baseline because no results were reported for infants and young children up to age 24 months.

Figure A 9 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/day), and change in weight.***

*** Risk of bias due to A: confounding; B: selection of participants into the study; C: measurement of the exposure; D: post-exposure interventions; E: missing data; F: measurement of the outcome; G: selection of the reported result; +: Low risk of bias; ?: Some concerns of risk of bias; −: High risk of bias; CI: confidence interval; d: day; oz: ounce; RE: random effects; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and change in weight in children. Overall, there was not a statistically significant difference in change in weight by 100% juice intake: −0.00 (95% CI: −0.04, 0.04). Risk of bias domains are also reported (see Table 13 for additional information).

Figure A 10 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/day), and change in weight, by total energy intake adjustment.^†††^

^†††^ adj: adjusted; CI: confidence interval; d: day; oz: ounce; RE: random effects; TEI: total energy intake; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and change in weight in children, by TEI adjustment. The plot shows that results adjusting for TEI do not significantly differ from those that do not adjust for TEI. In the TEI-unadjusted subgroup, the 95% CI includes 0; only one study adjusted for TEI.

Figure A 11 Meta-analysis of 100% juice intake at baseline, measured continuously (8 oz/day), and change in weight, by baseline weight status.^‡‡‡^

^‡‡‡^ CI: confidence interval; d: day; oz: ounce; OWO: overweight or obesity; RE: random effects; vertical dotted line shows null effect

This figure shows a forest plot summarizing the meta-analysis of 100% juice at baseline (measured continuously, per 8 oz/d intake) and change in weight in children, by baseline weight status. The plot shows that results for participants without OWO do not significantly differ from those with any weight status. In the “Any weight status” subgroup, the 95% CI includes 0; the “without OWO” subgroup only included one study.