# Appendix 4 Literature search strategy

## Searches from the existing reviews

Review A identified articles published between January 2000 and June 2019. For the complete search documentation, refer to:

Mayer-Davis E, Leidy H, Mattes R, . Beverage Consumption and Growth, Size, Body Composition, and Risk of Overweight and Obesity: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2020. 10.52570/NESR.DGAC2020.SR0401

Review B identified articles published between January 1980 and May 2023. These articles were included in one or both systematic reviews with meta-analysis conducted by the Committee (sugar-sweetened beverages and growth, body composition, and risk of obesity, and 100% juice and growth, body composition, and risk of obesity) and were not included in the systematic reviews for low- and no-calorie sweetened beverages, beverage patterns, or dairy milk and milk alternatives and growth, body composition, and risk of obesity. For the complete search documentation, refer to:

Fisher JO, Abrams SA, Andres A, . Complementary Feeding and Growth, Body Composition, and Risk of Obesity: A Systematic Review. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2024. 10.52570/NESR.DGAC2025.SR18

## Searches from the current review

### Search A

The search was conducted to identify articles on beverage consumption and gestational weight gain and postpartum weight change published between January 2000 and June 2019. This search was done because search terms for gestational weight gain were not included in the existing review search. The terms are included in Search C.

Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: June 25, 2019

Dates Covered: January 1, 2000 – June 25, 2019

Table A 4 Search for PubMed (Search A)

Search # | Concept | String
#1 | Beverages | “Beverages”[Mesh:NoExp] OR beverage[tiab] OR beverages[tiab] OR caloric drink* OR sports drink* OR protein drink* OR fortified drink* OR sweetened drink* OR sweet drink* OR sugary drink* OR dairy drink* OR chocolate drink* OR nutritional drink* OR smoothie*[tiab] OR protein shake* OR meal replacement*[tiab] OR carbonated drink*[tiab] OR soft drink*[tiab] OR soda[tiab] OR sodas[tiab] OR caffeinated drink*[tiab] OR “Drinking Water”[Mesh] OR drinking water[tiab] OR bottled water[tiab] OR “Carbonated Beverages”[Mesh] OR carbonated water[tiab] OR sparkling water[tiab] OR flavored water[tiab] OR flavoured water[tiab] OR flavoured drink[tiab] OR flavored drink* OR “Energy Drinks”[Mesh] OR energy drink*[tiab] OR sugar sweetened drink* OR “Fruit and Vegetable Juices”[Mesh] OR juice[tiab] OR juices[tiab] OR fruit drink* OR fizzy drink* OR “Coffee”[Mesh] OR coffee[tiab] OR “Tea”[Mesh] OR tea[tiab] OR “Milk”[Mesh:NoExp] OR milk[tiab] OR “Soy Milk”[Mesh] OR soymilk[tiab] OR “Buttermilk”[Mesh] OR buttermilk[tiab] OR “Whey”[Mesh] OR whey[tiab] OR liquid[tiab] OR liquids[tiab]
#2 | Pregnancy and postpartum period | “Pregnancy”[Mesh] OR “Pregnancy Complications”[Mesh] OR “Prenatal Exposure Delayed Effects”[Mesh] OR “Maternal Exposure”[Mesh] OR “pregnant women”[Mesh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR pre-natal[tiab] OR maternal[tiab] OR mother[tiab] OR mothers[tiab] OR “Mothers”[Mesh] OR postpartum[tiab] OR perinatal[tiab] OR peri-natal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation*[tiab] OR natal[tiab] OR antenatal[tiab] OR ante-natal[tiab] OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh] OR “Postpartum Period”[Mesh] OR postpartum[tiab] OR post-partum[tiab] OR perinatal OR peri-natal OR puerperium[tiab] OR postpartal OR post-partal OR postnatal OR post delivery[tiab] OR after birth[tiab] OR “Lactation”[Mesh] OR lactation[tiab] OR lactating[tiab] OR “Breast Feeding”[Mesh] OR breastfeeding[tiab] OR breast-feeding[tiab] OR breast feed* OR breast-feed*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breastfeed* OR “Milk, Human”[Mesh] OR human milk[tiab] OR nursing women[tiab]
#3 | Weight change | “Gestational Weight Gain”[Mesh] OR gestational weight gain[tiab] OR “Weight Gain”[Mesh:NoExp] OR weight gain[tiab] OR “Obesity”[Mesh] OR obesity[tiab] OR obese[tiab] OR overweight[tiab] OR “body size”[tiab] OR “Body Size”[Mesh] OR overnutrition[tiab] OR “Overnutrition”[Mesh:NoExp] OR adipos*[tiab] OR anthropometry[tiab] OR anthropometric*[tiab] OR “Adiposity”[Mesh] OR adipose[tiab] OR body weight[tiab] OR “Body Weight”[Mesh] OR “Body Composition”[Mesh] OR body fat[tiab] OR weight[ti] OR “Body Mass Index”[Mesh] OR body mass index[tiab] OR BMI[tiab] OR weight status[tiab] OR “Adipose Tissue”[Mesh] OR healthy weight[tiab] OR body fat mass[tiab] OR weight change[tiab] OR weight changes[tiab] OR “Weight Loss”[Mesh] OR weight loss*[tiab] OR weight reduc*[tiab] OR body weight[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR weight maint* OR “Diet, Reducing”[Mesh] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR (weight[tiab] AND (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain*[tiab] OR decreas*[tiab] OR watch OR control*[tiab] OR change*[tiab] OR gain[tiab]))
#4 | | #1 AND #2 AND #3
#5 | Limits | #4 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]); Filters: Publication date from 2000/01/01 to 2019/06/25; English

Database: Embase

Provider: Elsevier

Date(s) Searched: June 25, 2019

Dates Covered: January 1, 2000 – June 25, 2019

Table A 5 Search for Embase (Search A)

Search # | Concept | String
#1 | Beverages | ‘beverage’/mj OR ‘drinking water’/mj OR ‘carbonated beverage’/de OR ‘energy drink’/de OR ‘fruit and vegetable juice’/exp/mj OR ‘coffee’/exp/mj OR ‘milk’/mj OR ‘soybean milk’/de OR ‘buttermilk’/de OR ‘whey’/de OR beverage:ab,ti OR beverages:ab,ti OR ‘sports drink*’:ab,ti OR ‘protein drink*’:ab,ti OR ‘fortified drink*’:ab,ti OR ‘sweetened drink*’:ab,ti OR ‘sweet drink*’:ab,ti OR ‘sugary drink*’:ab,ti OR ‘dairy drink*’:ab,ti OR ‘chocolate drink*’:ab,ti OR ‘nutritional drink*’:ab,ti OR smoothie*:ab,ti OR ‘protein shake*’:ab,ti OR ‘meal replacement*’:ab,ti OR ‘carbonated drink*’:ab,ti OR ‘soft drink*’:ab,ti OR soda:ab,ti OR sodas:ab,ti OR ‘caffeinated drink*’:ab,ti OR ‘drinking water’:ab,ti OR ‘bottled water’:ab,ti OR ‘carbonated water’:ab,ti OR ‘sparkling water’:ab,ti OR ‘flavored water’:ab,ti OR ‘flavoured water’:ab,ti OR ‘flavoured drink’:ab,ti OR ‘flavored drink*’:ab,ti OR ‘energy drink*’:ab,ti OR ‘sugar sweetened drink*’:ab,ti OR juice:ab,ti OR juices:ab,ti OR ‘fruit drink*’:ab,ti OR ‘fizzy drink*’:ab,ti OR coffee:ab,ti OR tea:ab,ti OR milk:ab,ti OR soymilk:ab,ti OR buttermilk:ab,ti OR whey:ab,ti OR liquid:ab,ti OR liquids:ab,ti
#2 | Pregnancy and postpartum period | ‘pregnancy’/exp/mj OR ‘pregnancy complication’/exp/mj OR ‘prenatal exposure’/mj OR ‘maternal exposure’/mj OR ‘pregnant woman’/mj OR ‘mother’/mj OR ‘puerperium’/exp/mj OR ‘maternal nutrition’/mj OR ‘lactation’/mj OR ‘breast feeding’/exp/mj OR ‘breast milk’/exp/mj OR pregnancy:ab,ti OR ‘pre pregnancy’:ab,ti OR prenatal:ab,ti OR ‘pre natal’:ab,ti OR maternal:ab,ti OR mother:ab,ti OR mothers:ab,ti OR ‘pre conception’:ab,ti OR preconception:ab,ti OR ‘peri conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR antenatal:ab,ti OR ‘ante natal’:ab,ti OR postpartum:ab,ti OR post-partum:ab,ti OR perinatal:ab,ti OR ‘peri natal’:ab,ti OR puerperium:ab,ti OR postpartal:ab,ti OR post-partal:ab,ti OR postnatal:ab,ti OR ‘post delivery’:ab,ti OR ‘after birth’:ab,ti OR lactation:ab,ti OR lactating:ab,ti OR breastfeeding:ab,ti OR breast-feeding:ab,ti OR ‘breast feed*’:ab,ti OR breastfed:ab,ti OR ‘breast fed’:ab,ti OR breastfeed:ab,ti OR ‘human milk’:ab,ti OR ‘nursing women’:ab,ti
#3 | Weight change | ‘gestational weight gain’/mj OR ‘body weight gain’/de OR ‘obesity’/exp/mj OR ‘body size’/mj OR ‘overnutrition’/mj OR ‘body weight’/exp/mj OR ‘body composition’/exp/mj OR ‘body mass’/de OR ‘adipose tissue’/exp/mj OR ‘body weight loss’/exp/mj OR ‘weight loss program’/mj OR ‘weight trajectory (body weight)’/mj OR ‘low calorie diet’/exp/mj OR ‘gestational weight gain’:ab,ti OR ‘weight gain’:ab,ti OR obesity:ab,ti OR obese:ab,ti OR overweight:ab,ti OR ‘body size’:ab,ti OR overnutrition:ab,ti OR adipos*:ab,ti OR anthropometry:ab,ti OR anthropometric*:ab,ti OR adipose:ab,ti OR ‘body fat’:ab,ti OR weight:ab,ti OR ‘body mass index’:ab,ti OR bmi:ab,ti OR ‘weight status’:ab,ti OR ‘healthy weight’:ab,ti OR ‘body fat mass’:ab,ti OR ‘weight change’:ab,ti OR ‘weight changes’:ab,ti OR ‘weight loss*’:ab,ti OR ‘weight reduct*’:ab,ti OR ‘body weight’:ab,ti OR ‘weight maint*’:ab,ti OR ‘diet reduc*’:ab,ti OR ‘weight cycling’:ab,ti OR ‘weight decreas*’:ab,ti OR ‘weight watch*’:ab,ti OR ‘weight control*’:ab,ti OR ‘weight retention’:ab,ti OR (weight NEAR/4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain)):ab,ti
#4 | | #1 AND #2 AND #3
#5 | Limits | #4 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000–2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim) AND [2000–2019]/py

Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: June 25, 2019

Dates Covered: January 1, 2000 – June 25, 2019

Table A 6 Search for Cochrane CENTRAL (Search A)

Search # | Concept | String
#1 | Beverages | [mh ^Beverages] OR [mh “Drinking Water”] OR [mh “Carbonated Beverage”] OR [mh “Energy Drink”] OR [mh “Fruit and Vegetable Juice”] OR [mh Coffee] OR [mh ^Milk] OR (beverage OR beverages OR “sports drink” OR “protein drink” OR “fortified drink” OR “sweetened drink” OR “sweet drink” OR “sugary drink” OR “dairy drink” OR “chocolate drink” OR “nutritional drink” OR smoothie* OR “protein shake” OR “meal replacement” OR “carbonated drink” OR “soft drink” OR soda OR sodas OR “caffeinated drink” OR “drinking water” OR “bottled water” OR “carbonated water” OR “sparkling water” OR “flavored water” OR “flavoured water” OR “flavoured drink” OR “flavored drink*” OR “energy drink” OR “sugar sweetened drink” OR juice OR juices OR “fruit drink” OR “fizzy drink” OR coffee OR tea OR milk OR soymilk OR buttermilk OR whey OR liquid OR liquids):ti,ab,kw”
#2 | Pregnancy and postpartum period | [mh “Pregnancy”] OR [mh “Pregnancy Complications”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Mothers”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”] OR [mh “Postpartum Period”] OR [mh Lactation] OR [mh “Breast Feeding”] OR [mh “Milk, Human”] OR (pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth” OR lactation OR lactating OR breastfeeding OR breast-feeding OR breast feed* OR breast-feed* OR breastfed OR breast-fed OR breastfeed OR “human milk” OR “nursing women”):ti,ab,kw
#3 | Weight change | [mh “Gestational Weight Gain”] OR [mh ^“Weight Gain”] OR [mh Obesity] OR [mh “Body Size”] OR [mh ^Overnutrition] OR [mh Adiposity] OR [mh “Body Weight”] OR [mh “Body Composition”] OR [mh “Body Mass Index”] OR [mh “Adipose Tissue”] OR [mh “Weight Loss”] OR [mh “Weight Reduction Programs”] OR [mh “Body-Weight Trajectory”] OR [mh “Diet, Reducing”] OR (“gestational weight gain” OR “weight gain” OR obesity OR obese OR overweight OR “body size” OR overnutrition OR adipos* OR anthropometry OR anthropometric* OR adipose OR “body weight” OR “body fat” OR weight OR “body mass index” OR BMI OR “weight status” OR “healthy weight” OR “body fat mass” OR “weight change” OR “weight changes” OR “weight loss*” OR “weight reduct*” OR “body weight” OR “weight maint*” OR “diet reduc*” OR “weight cycling” OR “weight decreas*” OR “weight watch*” OR “weight control*” OR “weight retention”):ti,ab,kw OR ((weight NEAR/4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain)):ti,ab,kw
#4 | | #1 AND #2 AND #3
| Limits | Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

Database: CINAHL

Provider: EBSCO

Date(s) Searched: June 25, 2019

Dates Covered: January 1, 2000 – June 25, 2019

Table A 7 Search for CINAHL (Search A)

Search # | Concept | String
#1 | Beverages | (MH “Beverages+” OR MH “Water Supply”) OR (beverage OR beverages OR “sports drink*” OR “protein drink*” OR “fortified drink*” OR “sweetened drink*” OR “sweet drink*” OR “sugar drink*” OR “sugary drink*” OR “dairy drink*” OR “chocolate drink*” OR “nutritional drink*” OR smoothie* OR “protein shake*” OR “meal replacement*” OR “carbonated drink*” OR “soft drink*” OR soda OR sodas OR “caffeinated drink*” OR “drinking water” OR “bottled water*” OR “carbonated water*” OR “sparkling water*” OR “flavored water*” OR “flavoured water*” OR “flavoured drink*” OR “flavored drink*” OR “energy drink*” OR “sugar sweetened drink*” OR juice OR juices OR “fruit drink*” OR “fizzy drink*” OR coffee OR tea OR milk OR soymilk OR buttermilk OR whey OR liquid*)
#2 | Pregnancy and postpartum period | (MH “Pregnancy+”) OR (MH “Pregnancy Complications”) OR (MH “Prenatal Exposure Delayed Effects”) OR (MH “Maternal Exposure”) OR (MH “Expectant Mothers”) OR (MH “Mothers”) OR (MH “Puerperium”) OR (MH “Maternal Nutritional Physiology”) OR (MH “Postnatal Period”) OR (MH “Lactation”) OR (MH “Breast Feeding”) OR (MH “Milk, Human”) OR pregnancy OR pre-pregnancy OR prenatal OR pre-natal OR maternal OR mother OR mothers OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation* OR natal OR antenatal OR ante-natal OR puerperium OR postpartum OR post-partum OR perinatal OR peri-natal OR puerperium OR postpartal OR post-partal OR postnatal OR “post delivery” OR “after birth” OR lactation OR lactating OR breastfeeding OR breast-feeding OR breast feed* OR breast-feed* OR breastfed OR breast-fed OR breastfeed OR “human milk” OR “nursing women”
#3 | Weight change | (MH “Gestational Weight Gain”) OR (MH “Weight Gain”) OR (MH “Obesity”) OR (MH “Body Size”) OR (MH “Body Weight”) OR (MH “Body Composition”) OR (MH “Body Mass Index”) OR (MH “Adipose Tissue”) OR (MH “Weight Loss”) OR (MH “Weight Reduction Programs”) OR (MH “Diet, Reducing”) OR “gestational weight gain” OR “weight gain” OR obesity OR obese OR overweight OR “body size” OR overnutrition OR adipos* OR anthropometry OR anthropometric* OR adipose OR “body weight” OR “body fat” OR weight OR “body mass index” OR BMI OR “weight status” OR “healthy weight” OR “body fat mass” OR “weight change” OR “weight changes” OR “weight loss*” OR “weight reduct*” OR “body weight” OR “weight maint*” OR “diet reduc*” OR “weight cycling” OR “weight decreas*” OR “weight watch*” OR “weight control*” OR “weight retention” OR (weight N4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain))
#4 | | S1 AND S2 AND S3
#5 | Limits | S4 NOT ( MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication ); Limiters - Published Date: 20000101–20190625; Peer Reviewed; English Language; Human

### Search B

This search identified articles published between January 2000 and June 2019. The terms cover growth, body composition, and risk of obesity terms included in Search C, but not included in the search from the existing review. This search was only run in PubMed.

Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: July 19, 2021

Dates Covered: January 1, 2000 to December 31, 2019

Table A 8 Search for PubMed (Search B)

Search # | Concept | String
#1 | Growth, body composition, and risk of obesity (updated 2021) | “Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[Mesh] OR “Overnutrition”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometric*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR anthropometry[tiab] OR anthropometric[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin; folds[tiab] OR skinfold[tiab] OR skinfolds[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR weight maint* OR “Diet, Reducing”[Mesh] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR (weight[tiab] AND (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain*[tiab] OR decreas*[tiab] OR watch OR control*[tiab] OR change*[tiab] OR gain[tiab])) OR “Growth Charts”[Mesh] OR growth chart[tiab] OR growth charts[tiab] OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#2 | Growth, body composition, and risk of obesity (updated 2019) | (“Body Composition”[Mesh] OR body composition[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR healthy weight[tiab] OR underweight[tiab] OR wasting[tiab] OR failure to thrive[tiab] OR “Waist Circumference”[Mesh] OR waist circumference[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR thigh circumference[tiab] OR neck circumference[tiab] OR “Body Height”[Mesh:NoExp] OR body height[tiab] OR stunting[tiab] OR stunted[tiab] OR “Overweight”[Mesh] OR overweight[tiab] OR obesity[tiab] OR obese[tiab] OR “Body Mass Index”[Mesh] OR body mass index[tiab] OR BMI[tiab] OR body fat[tiab]
#3 | Beverages | “Beverages”[Mesh:NoExp] OR beverage[tiab] OR beverages[tiab] OR sports drink* OR protein drink* OR fortified drink* OR sweetened drink* OR sweet drink* OR sugary drink* OR dairy drink* OR chocolate drink* OR nutritional drink* OR smoothie*[tiab] OR protein shake* OR meal replacement*[tiab] OR carbonated drink*[tiab] OR soft drink*[tiab] OR soda[tiab] OR sodas[tiab] OR caffeinated drink*[tiab] OR “Drinking Water”[Mesh] OR drinking water[tiab] OR bottled water[tiab] OR “Carbonated Beverages”[Mesh] OR carbonated water[tiab] OR sparkling water[tiab] OR flavored water[tiab] OR flavoured water[tiab] OR flavoured drink[tiab] OR flavored drink* OR “Energy Drinks”[Mesh] OR energy drink*[tiab] OR sugar sweetened drink* OR “Fruit and Vegetable Juices”[Mesh] OR juice[tiab] OR juices[tiab] OR fruit drink* OR fizzy drink* OR “Coffee”[Mesh] OR coffee[tiab] OR “Tea”[Mesh] OR tea[tiab] OR “Milk”[Mesh:NoExp] OR milk[tiab] OR “Soy Milk”[Mesh] OR soymilk[tiab] OR “Buttermilk”[Mesh] OR buttermilk[tiab] OR “Whey”[Mesh] OR whey[tiab] OR liquid[tiab] OR liquids[tiab]
#4 | | (#1 NOT #2) AND #3
#5 | | #4 NOT ((“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh]))) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]); Language: English; Publication Year:2000–2019

### Search C

This search was conducted to identify articles published since the existing review. This search was used in both this review and in systematic reviews that examine the relationship between dairy and milk alternatives and growth, body composition, and risk of obesity; low- and no-calorie sweetened beverages and growth, body composition, and risk of obesity; beverage patterns and growth, body composition, and risk of obesity; and sugar sweetened beverages and growth, body composition, and risk of obesity. The search captured articles published from June 2019 through May 2023. The search was first run on December 12, 2021, and then periodically run using NESR’s continuous evidence monitoring methods^*^ until May 31, 2023.

* USDA Nutrition Evidence Systematic Review Branch. Chapter 10: Continuous Evidence Monitoring. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview.

Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: December 12, 2021 (initial search); December 16, 2021 to May 31, 2023 (continuous evidence monitoring)

Dates Covered: June 20, 2019 – May 31, 2023

Table A 9 Search for PubMed (Search C)

Search # | Concept | String
#1 | Growth, body composition, and risk of obesity | “Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[MeSH:NoExp] OR “Body Fat Distribution”[Mesh] OR “Body Mass Index”[Mesh] OR “Body Size”[Mesh] OR “Skinfold Thickness”[Mesh] OR “Waist-Hip Ratio”[Mesh] OR “Overnutrition”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR waist to hip ratio[tiab] OR waist hip ratio[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR “Diet, Reducing”[Mesh] OR weight gain[tiab] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR weight management[tiab] OR (weight[tiab] AND (maint*[tiab] OR reduc*[tiab] OR loss*[tiab] OR chang*[tiab])) OR “Growth Charts”[Mesh] OR growth chart*[tiab]OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#2 | Beverages | (“Beverages”[Mesh:NoExp] OR “Sugar Sweetened Beverages”[MeSH] OR beverage*[tiab] OR sports drink*[tiab] OR fortified drink*[tiab] OR sweetened drink*[tiab] OR sweet drink*[tiab] OR sugary drink*[tiab] OR dairy drink*[tiab] OR chocolate drink*[tiab] OR smoothie*[tiab] OR carbonated drink*[tiab] OR soft drink*[tiab] OR soda[tiab] OR sodas[tiab] OR caffeinated drink*[tiab] OR “Drinking Water”[Mesh] OR drinking water[tiab] OR bottled water[tiab] OR “Carbonated Beverages”[Mesh] OR carbonated water[tiab] OR sparkling water[tiab] OR flavored water[tiab] OR flavoured water[tiab] OR flavoured drink*[tiab] OR flavored drink*[tiab] OR “Energy Drinks”[Mesh] OR energy drink*[tiab] OR “Fruit and Vegetable Juices”[Mesh] OR juice[tiab] OR juices[tiab] OR fruit drink*[tiab] OR fizzy drink*[tiab] OR “Coffee”[Mesh] OR coffee[tiab] OR “Tea”[Mesh] OR tea[tiab] OR “Milk”[Mesh:NoExp] OR milk[tiab] OR “Soy Milk”[Mesh] OR soymilk[tiab] OR “Buttermilk”[Mesh] OR buttermilk[tiab] OR liquid[tiab] OR liquids[tiab])
#3 | | #1 AND #2
#4 | Limits | #3 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Language: English; Publication Date: 6/20/2019 - present

Database: Embase

Provider: Elsevier

Date(s) Searched: December 12, 2021 (initial search); December 16, 2021- May 31, 2023 (continuous evidence monitoring)

Dates Covered: June 20, 2019 – May 31, 2023

Table A 10 Search for Embase (Search C)

Search # | Concept | String
#1 | Growth, body composition, and risk of obesity | ‘adipose tissue’/exp OR ‘body composition’/exp OR ‘anthropometry’/de OR ‘body mass’/exp OR ‘anthropometric parameters’/exp OR ‘skinfold thickness’/exp OR ‘overnutrition’/exp OR ‘growth’/de OR ‘anthropometr*’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘lean mass’:ab,ti OR ‘obese’:ab,ti OR ‘obesity’:ab,ti OR ‘underweight’:ab,ti OR ‘overweight’:ab,ti OR ‘weight status’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘calf circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘waist circumference’:ab,ti OR ‘waist to hip ratio’:ab,ti OR ‘waist hip ratio’:ab,ti OR ‘body mass index’:ab,ti OR ‘BMI’:ab,ti OR ‘adipos*’:ab,ti OR ‘body weight’:ab,ti OR ‘body height’:ab,ti OR ‘body size’:ab,ti OR ‘body composition’:ab,ti OR ‘overnutrition’:ab,ti OR ‘wasting’:ab,ti OR ‘healthy weight’:ab,ti OR ‘skin fold*’:ab,ti OR ‘skinfold*’:ab,ti; OR ‘body weight management’/exp OR ‘body weight change’/exp OR ‘weight gain*’:ab,ti OR ‘diet reduc*’:ab,ti OR ‘weight cycling’:ab,ti OR ‘weight watch*’:ab,ti OR ‘weight control*’:ab,ti OR ‘weight retention’:ab,ti OR ‘weight management’:ab,ti OR (weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)):ab,ti; OR ‘weight chart’/exp OR ‘growth chart*’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘weight for height’:ab,ti OR ‘stature for age’:ab,ti OR ‘weight for age’:ab,ti OR ‘height for age’:ab,ti OR ‘length for age’:ab,ti OR ‘weight for length’:ab,ti OR ‘failure to thrive’:ab,ti
#2 | Beverages | ‘beverages’/de OR ‘sweetened beverage’/exp OR ‘drinking water’/exp OR ‘carbonated beverages’/exp OR ‘carbonated water’/exp OR ‘energy drink’/exp OR ‘fruit and vegetable juice’/exp OR ‘coffee’/exp OR ‘tea’/exp OR ‘milk’/de OR ‘soybean milk’/exp OR ‘buttermilk’/exp OR ‘beverage’:ab,ti OR ‘beverages’:ab,ti OR ‘sports drink*’:ab,ti OR ‘fortified drink*’:ab,ti OR ‘sweetened drink*’:ab,ti OR ‘sweet drink*’:ab,ti OR ‘sugary drink*’:ab,ti OR ‘dairy drink*’:ab,ti OR ‘chocolate drink*’:ab,ti OR smoothie*:ab,ti OR ‘carbonated drink*’:ab,ti OR ‘soft drink*’:ab,ti OR ‘soda’:ab,ti OR ‘sodas’:ab,ti OR ‘caffeinated drink*’:ab,ti OR ‘drinking water’:ab,ti OR ‘bottled water’:ab,ti OR ‘carbonated water’:ab,ti OR ‘sparkling water’:ab,ti OR ‘flavored water’:ab,ti OR ‘flavoured water’:ab,ti OR ‘flavoured drink’:ab,ti OR ‘flavored drink*’:ab,ti OR ‘energy drink*’:ab,ti OR ‘juice’:ab,ti OR ‘juices’:ab,ti OR ‘fruit drink*’:ab,ti OR ‘fizzy drink*’:ab,ti OR ‘coffee’:ab,ti OR ‘tea’:ab,ti OR ‘milk’:ab,ti OR ‘soymilk’:ab,ti OR ‘soy milk’:ab,ti OR ‘buttermilk’:ab,ti OR ‘liquid’:ab,ti OR ‘liquids’:ab,ti
#3 | | #1 AND #2
#4 | Limits | #3 AND ([article]/lim OR [article in press]/lim) NOT ([animals]/lim NOT ([animals]/lim AND [humans]/lim)) AND [english]/lim NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR ‘retraction of publication’:ab,ti OR ‘retraction notice’:ti OR ‘retracted publication’:ab,ti OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim OR ‘practice guideline’:ti) AND [2019–2023]/py

Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Provider: John Wiley & Sons

Date(s) Searched: December 12, 2021 (initial search); December 16, 2021- May 31, 2023 (continuous evidence monitoring)

Dates Covered: June 20, 2019 – May 31, 2023

Table A 11 Search for Cochrane CENTRAL (Search C)

Search # | Concept | String
#1 | Growth, body composition, and risk of obesity | [mh “Adipose Tissue”] OR [mh “Body Composition”] OR [mh ^“Body Weights and Measures”] OR [mh “Body Fat Distribution”] OR [mh “Body Mass Index”] OR [mh “Body Size”] OR [mh “Skinfold Thickness”] OR [mh “Waist-Hip Ratio”] OR [mh Overnutrition] OR [mh ^Growth] OR (anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds):ti,ab,kw OR [mh “Weight Reduction Programs”] OR [mh “Body-Weight Trajectory”] OR [mh “Weight Gain”] OR [mh ^“Weight Loss”] OR [mh “Diet, Reducing”] OR (“diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”):ti,ab,kw OR ((weight NEAR/4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*)) OR [mh “Growth Charts”] OR “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”):ti,ab,kw
#2 | Beverages | [mh ^“Beverages”] OR [mh “Sugar Sweetened Beverage”] OR [mh “Drinking Water”] OR [mh “Carbonated Beverages”] OR [mh “Energy Drinks”] OR [mh “Fruit and Vegetable Juices”] OR [mh “Coffee”] OR [mh “Tea”] OR [mh ^“Milk”] OR [mh “Soy Milk”] OR [mh “Buttermilk”] OR (beverage OR beverages OR “sports drink*” OR “fortified drink*” OR “sweetened drink*” OR “sweet drink*” OR “sugary drink*” OR “dairy drink*” OR “chocolate drink*” OR smoothie* OR “carbonated drink*” OR “soft drink*” OR soda OR sodas OR “caffeinated drink*” OR “drinking water” OR “bottled water” OR “carbonated water” OR “sparkling water” OR “flavored water” OR “flavoured water” OR “flavoured drink” OR “flavored drink*” OR “energy drink*” OR juice OR juices OR “fruit drink*” OR “fizzy drink*” OR coffee OR tea OR milk OR soymilk OR “soy milk” OR buttermilk OR liquid OR liquids):ti,ab,kw
#3 | | #1 AND #2
#4 | Limits | In Trials, word variations searched, year first published 2019–2023

Database: CINAHL

Provider: EBSCO

Date(s) Searched: December 12, 2021 (initial search); December 16, 2021- May 31, 2023 (continuous evidence monitoring)

Dates Covered: June 20, 2019 – May 31, 2023

Table A 12 Search for CINAHL (Search C)

Search # | Concept | String
#1 | Growth, body composition, and risk of obesity | (MH “Adipose Tissue+”) OR (MH “Body Composition+”) OR (MH “Body Weights and Measures”) OR (MH “Arm Circumference”) OR (MH “Body Height”) OR (MH “Body Mass Index”) OR (MH “Body Size”) OR (MH “Body Weight+”) OR (MH “Crown-Rump Length”) OR (MH “Waist Circumference”) OR (MH “Waist-Hip Ratio”) OR (MH “Skinfold Thickness”) OR (MH “Obesity+”) OR (MH “Overnutrition”) OR (MH “Growth”) OR (TI anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (AB anthropometr* OR “body fat” OR “fat mass” OR “fat free mass” OR “lean mass” OR obese OR obesity OR underweight OR overweight OR “weight status” OR “head circumference” OR “arm circumference” OR “calf circumference” OR “neck circumference” OR “thigh circumference” OR “waist circumference” OR “waist to hip ratio” OR “waist hip ratio” OR “body mass index” OR BMI OR adipos* OR “body weight” OR “body height” OR “body size” OR “body composition” OR overnutrition OR wasting OR “healthy weight” OR “skin fold” OR “skin folds” OR skinfold OR skinfolds) OR (MH “Weight Reduction Programs”) OR (MH “Body Weight Changes”) OR (MH “Weight Gain+”) OR (MH “Weight Loss”) OR (MH “Diet, Reducing”) OR (TI “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”) OR (AB “diet reduc*” OR “weight cycling” OR “weight watch*” OR “weight control*” OR “weight retention” OR “weight management”) OR (TI (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*))) OR (AB (weight N4 (decreas* OR gain* OR maint* OR reduc* OR loss* OR chang*))) OR (TI “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”) OR (AB “growth chart*” OR stunting OR stunted OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “length for age” OR “weight for length” OR “failure to thrive”)
#2 | Beverages | (MH “Sweetened Beverages”) OR (MH “Water+”) OR (MH “Carbonated Beverages”) OR (MH “Energy Drinks”) OR (MH “Fruit Juices”) OR (MH “Coffee”) OR (MH “Tea”) OR (MH “Milk”) OR (MH “Milk Substitutes+”) OR TI (beverage* OR sports drink* OR fortified drink* OR sweetened drink* OR sweet drink* OR sugary drink* OR dairy drink* OR chocolate drink* OR smoothie* OR carbonated drink* OR soft drink* OR soda OR sodas OR caffeinated drink* OR drinking water OR bottled water OR carbonated water OR sparkling water OR flavored water OR flavoured water OR flavoured drink* OR flavored drink* OR energy drink* OR juice OR juices OR fruit drink* OR fizzy drink* OR coffee OR tea OR milk OR soymilk OR buttermilk OR liquid OR liquids) OR AB (beverage* OR sports drink* OR fortified drink* OR sweetened drink* OR sweet drink* OR sugary drink* OR dairy drink* OR chocolate drink* OR smoothie* OR carbonated drink* OR soft drink* OR soda OR sodas OR caffeinated drink* OR drinking water OR bottled water OR carbonated water OR sparkling water OR flavored water OR flavoured water OR flavoured drink* OR flavored drink* OR energy drink* OR juice OR juices OR fruit drink* OR fizzy drink* OR coffee OR tea OR milk OR soymilk OR buttermilk OR liquid OR liquids)
#3 | | S1 AND S2
#4 | Limits | S3 NOT ((MH “Animals+”) OR (MH “Animal Studies”)) NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication”)); Limiters - English Language, Expanders - Apply equivalent subjects, Published Date: 20190601–20230531