# Appendix 2 Conclusion statements from the existing systematic review

Table A 2 Conclusion statements from the existing systematic review for the research question: What is the relationship between 100% juice consumption and growth, body composition, and risk of obesity?

Citation | Conclusion statements and grades
Mayer-Davis E, Leidy H, Mattes R, Naimi T, Novotny R, Schneeman B, Kingshipp BJ, Spill M, Cole NC, Bahnfleth CL, Butera G, Terry N, Obbagy J. Beverage Consumption and Growth, Size, Body Composition, and Risk of Overweight and Obesity: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://doi.org/10.52570/NESR.DGAC2020.SR0401 | Limited evidence suggests 100% juice intake in children is not associated with adiposity or height in children. (Grade: Limited); Limited evidence suggests 100% juice consumption is not associated with measures of adiposity in adults. (Grade: Limited)