# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
BMIZ: BMI z-score
FFQ: Food frequency questionnaire
FNS: Food and Nutrition Service
HDI: Human Development Index
HHS: United States Department of Health and Human Services
IOM: Institute of Medicine
NESR: Nutrition Evidence Systematic Review
NGAD: Nutrition Guidance and Analysis Division
PCS: Prospective cohort study
RCT: Randomized controlled trial
SEP: Socioeconomic position
TEI: Total energy intake
USDA: United States Department of Agriculture