# References of the articles included in the systematic review

1 Berkey CS, Rockett HR, Field AE, Gillman MW, Colditz GA. Sugar-added beverages and adolescent weight change. Obes Res. 2004;12(5):778–88. Available at: 10.1038/oby.2004.94.15166298
2 Blum JW, Jacobsen DJ, Donnelly JE. Beverage consumption patterns in elementary school aged children across a two-year period. J Am Coll Nutr. 2005;24(2):93–8. Available at: 10.1080/07315724.2005.10719449.15798075
3 Davis JN, Asigbee FM, Markowitz AK, Consumption of artificial sweetened beverages associated with adiposity and increasing HbA1c in Hispanic youth. Clin Obes. 2018;8(4):236–243. Available at: 10.1111/cob.12260.29896938
4 Dong D, Bilger M, van Dam RM, Finkelstein EA. Consumption Of Specific Foods And Beverages And Excess Weight Gain Among Children And Adolescents. Health Aff (Millwood). 2015;34(11):1940–8. Available at: 10.1377/hlthaff.2015.0434.26526253
5 Field AE, Sonneville KR, Falbe J, Association of sports drinks with weight gain among adolescents and young adults. Obesity (Silver Spring). 2014;22(10):2238–43. Available at: 10.1002/oby.20845.25044989
6 Haines J, Neumark-Sztainer D, Wall M, Story M. Personal, behavioral, and environmental risk and protective factors for adolescent overweight. Obesity (Silver Spring). 2007;15(11):2748–60. Available at: 10.1038/oby.2007.327.18070766
7 Hasnain SR, Singer MR, Bradlee ML, Moore LL. Beverage intake in early childhood and change in body fat from preschool to adolescence. Child Obes. 2014;10(1):42–9. Available at: 10.1089/chi.2013.0004.24450382
8 Johnson L, Mander AP, Jones LR, Emmett PM, Jebb SA. Is sugar-sweetened beverage consumption associated with increased fatness in children? Nutrition. 2007;23(7–8):557–63. Available at: 10.1016/j.nut.2007.05.005.17616342
9 Kral TV, Stunkard AJ, Berkowitz RI, Stallings VA, Moore RH, Faith MS. Beverage consumption patterns of children born at different risk of obesity. Obesity (Silver Spring). 2008;16(8):1802–8. Available at: 10.1038/oby.2008.287.18535546
10 Laska MN, Murray DM, Lytle LA, Harnack LJ. Longitudinal associations between key dietary behaviors and weight gain over time: transitions through the adolescent years. Obesity (Silver Spring). 2012;20(1):118–25. Available at: 10.1038/oby.2011.179.21701567
11 Ludwig DS, Peterson KE, Gortmaker SL. Relation between consumption of sugar-sweetened drinks and childhood obesity: a prospective, observational analysis. Lancet. 2001;357(9255):505–8. Available at: 10.1016/S0140-6736(00)04041-1.11229668
12 Macintyre AK, Marryat L, Chambers S. Exposure to liquid sweetness in early childhood: artificially-sweetened and sugar-sweetened beverage consumption at 4–5 years and risk of overweight and obesity at 7–8 years. Pediatr Obes. 2018;13(12):755–765. Available at: 10.1111/ijpo.12284.29624909
13 Newby PK, Peterson KE, Berkey CS, Leppert J, Willett WC, Colditz GA. Beverage consumption is not associated with changes in weight and body mass index among low-income preschool children in North Dakota. J Am Diet Assoc. 2004;104(7):1086–94. Available at: 10.1016/j.jada.2004.04.020.15215766
14 Striegel-Moore RH, Thompson D, Affenito SG, Correlates of beverage intake in adolescent girls: the National Heart, Lung, and Blood Institute Growth and Health Study. J Pediatr. 2006;148(2):183–7. Available at: 10.1016/j.jpeds.2005.11.025.16492426
15 Vanselow MS, Pereira MA, Neumark-Sztainer D, Raatz SK. Adolescent beverage habits and changes in weight over time: findings from Project EAT. Am J Clin Nutr. 2009;90(6):1489–95. Available at: 10.3945/ajcn.2009.27573.19864412
16 Zheng M, Allman-Farinelli M, Heitmann BL, Liquid versus solid energy intake in relation to body composition among Australian children. J Hum Nutr Diet. 2015;28 Suppl 2:70–9. Available at: 10.1111/jhn.12223.24548259
17 Zheng M, Rangan A, Allman-Farinelli M, Rohde JF, Olsen NJ, Heitmann BL. Replacing sugary drinks with milk is inversely associated with weight gain among young obesity-predisposed children. Br J Nutr. 2015;114(9):1448–55. Available at: 10.1017/S0007114515002974.26328600
18 Bes-Rastrollo M, Sanchez-Villegas A, Gomez-Gracia E, Martinez JA, Pajares RM, Martinez-Gonzalez MA. Predictors of weight gain in a Mediterranean cohort: the Seguimiento Universidad de Navarra Study 1. Am J Clin Nutr. 2006;83(2):362–70; quiz 394–5. Available at: 10.1093/ajcn/83.2.362.16469996
19 Bes-Rastrollo M, van Dam RM, Martinez-Gonzalez MA, Li TY, Sampson LL, Hu FB. Prospective study of dietary energy density and weight gain in women. Am J Clin Nutr. 2008;88(3):769–77. Available at: 10.1093/ajcn/88.3.769.18779295
20 Bonnet F, Tavenard A, Esvan M, Consumption of a Carbonated Beverage with High-Intensity Sweeteners Has No Effect on Insulin Sensitivity and Secretion in Nondiabetic Adults. J Nutr. 2018;148(8):1293–1299. Available at: 10.1093/jn/nxy100.29982723
21 Buso MEC, Brouwer-Brolsma EM, Naomi ND, Dose-Response and Substitution Analyzes of Sweet Beverage Consumption and Body Weight in Dutch Adults: The Lifelines Cohort Study. Front Nutr. 2022;9:889042. Available at: 10.3389/fnut.2022.889042.35832052
22 Chen L, Appel LJ, Loria C, Reduction in consumption of sugar-sweetened beverages is associated with weight loss: the PREMIER trial. Am J Clin Nutr. 2009;89(5):1299–306. Available at: 10.3945/ajcn.2008.27240.19339405
23 Duffey KJ, Steffen LM, Van Horn L, Jacobs DR, Jr., Popkin BM. Dietary patterns matter: diet beverages and cardiometabolic risks in the longitudinal Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. 2012;95(4):909–15. Available at: 10.3945/ajcn.111.026682.22378729
24 Ferreira-Pego C, Babio N, Bes-Rastrollo M, Frequent Consumption of Sugar- and Artificially Sweetened Beverages and Natural and Bottled Fruit Juices Is Associated with an Increased Risk of Metabolic Syndrome in a Mediterranean Population at High Cardiovascular Disease Risk. J Nutr. 2016;146(8):1528–36. Available at: 10.3945/jn.116.230367.27358413
25 Fowler SP, Williams K, Hazuda HP. Diet soda intake is associated with long-term increases in waist circumference in a biethnic cohort of older adults: the San Antonio Longitudinal Study of Aging. J Am Geriatr Soc. 2015;63(4):708–15. Available at: 10.1111/jgs.13376.25780952
26 Fowler SP, Williams K, Resendez RG, Hunt KJ, Hazuda HP, Stern MP. Fueling the obesity epidemic? Artificially sweetened beverage use and long-term weight gain. Obesity (Silver Spring). 2008;16(8):1894–900. Available at: 10.1038/oby.2008.284.18535548
27 Garduno-Alanis A, Malyutina S, Pajak A, Association between soft drink, fruit juice consumption and obesity in Eastern Europe: cross-sectional and longitudinal analysis of the HAPIEE study. J Hum Nutr Diet. 2020;33(1):66–77. Available at: 10.1111/jhn.12696.31475413
28 Gearon E, Peeters A, Ng W, Hodge A, Backholer K. Diet and physical activity as possible mediators of the association between educational attainment and body mass index gain among Australian adults. Int J Public Health. 2018;63(7):883–893. Available at: 10.1007/s00038-018-1100-z.29687156
29 Hinkle SN, Rawal S, Bjerregaard AA, A prospective study of artificially sweetened beverage intake and cardiometabolic health among women at high risk. Am J Clin Nutr. 2019;110(1):221–232. Available at: 10.1093/ajcn/nqz094.31172169
30 Konieczna J, Romaguera D, Pereira V, Longitudinal association of changes in diet with changes in body weight and waist circumference in subjects at high cardiovascular risk: the PREDIMED trial. Int J Behav Nutr Phys Act. 2019;16(1):139. Available at: 10.1186/s12966-019-0893-3.31882021
31 Ma J, McKeown NM, Hwang SJ, Hoffmann U, Jacques PF, Fox CS. Sugar-Sweetened Beverage Consumption Is Associated With Change of Visceral Adipose Tissue Over 6 Years of Follow-Up. Circulation. 2016;133(4):370–7. Available at: 10.1161/CIRCULATIONAHA.115.018704.26755505
32 Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Effects on weight loss in adults of replacing diet beverages with water during a hypoenergetic diet: a randomized, 24-wk clinical trial. Am J Clin Nutr. 2015;102(6):1305–12. Available at: 10.3945/ajcn.115.109397.26537940
33 Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Effects of replacing diet beverages with water on weight loss and weight maintenance: 18-month follow-up, randomized clinical trial. Int J Obes (Lond). 2018;42(4):835–840. Available at: 10.1038/ijo.2017.306.29633983
34 Maersk M, Belza A, Stodkilde-Jorgensen H, Sucrose-sweetened beverages increase fat storage in the liver, muscle, and visceral fat depot: a 6-mo randomized intervention study. Am J Clin Nutr. 2012;95(2):283–9. Available at: 10.3945/ajcn.111.022533.22205311
35 Mozaffarian D, Hao T, Rimm EB, Willett WC, Hu FB. Changes in diet and lifestyle and long-term weight gain in women and men. N Engl J Med. 2011;364(25):2392–404. Available at: 10.1056/NEJMoa1014296.21696306
36 Nettleton JA, Lutsey PL, Wang Y, Lima JA, Michos ED, Jacobs DR, Jr. Diet soda intake and risk of incident metabolic syndrome and type 2 diabetes in the Multi-Ethnic Study of Atherosclerosis (MESA). Diabetes Care. 2009;32(4):688–94. Available at: 10.2337/dc08-1799.19151203
37 Pan A, Malik VS, Hao T, Willett WC, Mozaffarian D, Hu FB. Changes in water and beverage intake and long-term weight changes: results from three prospective cohort studies. Int J Obes (Lond). 2013;37(10):1378–85. Available at: 10.1038/ijo.2012.225.23318721
38 Peters JC, Wyatt HR, Foster GD, The effects of water and non-nutritive sweetened beverages on weight loss during a 12-week weight loss treatment program. Obesity (Silver Spring). 2014;22(6):1415–21. Available at: 10.1002/oby.20737.24862170
39 Peters JC, Beck J, Cardel M, The effects of water and non-nutritive sweetened beverages on weight loss and weight maintenance: A randomized clinical trial. Obesity (Silver Spring). 2016;24(2):297–304. Available at: 10.1002/oby.21327.26708700
40 Qi Q, Chu AY, Kang JH, Sugar-sweetened beverages and genetic risk of obesity. N Engl J Med. 2012;367(15):1387–96. Available at: 10.1056/NEJMoa1203039.22998338
41 Schulze MB, Manson JE, Ludwig DS, Sugar-sweetened beverages, weight gain, and incidence of type 2 diabetes in young and middle-aged women. JAMA. 2004;292(8):927–34. Available at: 10.1001/jama.292.8.927.15328324
42 Stern D, Middaugh N, Rice MS, Changes in Sugar-Sweetened Soda Consumption, Weight, and Waist Circumference: 2-Year Cohort of Mexican Women. Am J Public Health. 2017;107(11):1801–1808. Available at: 10.2105/AJPH.2017.304008.28933937
43 Tate DF, Turner-McGrievy G, Lyons E, Replacing caloric beverages with water or diet beverages for weight loss in adults: main results of the Choose Healthy Options Consciously Everyday (CHOICE) randomized clinical trial. Am J Clin Nutr. 2012;95(3):555–63. Available at: 10.3945/ajcn.111.026278.22301929
44 Vazquez-Duran M, Orea-Tejeda A, Castillo-Martinez L, Cano-Garcia A, Tellez-Olvera L, Keirns-Davis C. A randomized control trial for reduction of caloric and non-caloric sweetened beverages in young adults: effects in weight, body composition and blood pressure. Nutr Hosp. 2016;33(6):1372–1378. Available at: 10.20960/nh.797.28000468
45 Davis JN, Shearrer GE, Tao W, Hurston SR, Gunderson EP. Dietary variables associated with substantial postpartum weight retention at 1-year among women with GDM pregnancy. BMC Obes. 2017;4:31. Available at: 10.1186/s40608-017-0166-0.28794888