# Summary of conclusion statements and grades

The Dietary Guidelines Advisory Committee answered the systematic review question, “What is the relationship between low- and no-calorie sweetened beverage consumption and growth, body composition, and risk of obesity?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. It does not draw implications and should not be interpreted as dietary guidance.

### Children and adolescents

Low- and no-calorie sweetened beverage consumption by children and adolescents may not be associated with growth, body composition, and risk of obesity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

### Adults and older adults

Low- and no-calorie sweetened beverage consumption by adults and older adults, compared with water or lower amounts of low- and no-calorie sweetened beverages, is not associated with a change in body composition and risk of obesity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

### Individuals during pregnancy and postpartum

A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened beverage consumption during pregnancy and adequacy of gestational weight gain because there is no evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened beverage consumption during postpartum and postpartum weight change because there is not enough evidence available. (Grade: Grade Not Assignable)

## Research recommendations

To address the limitations of this body of evidence, several research recommendations have been identified:

1. Increase the amount and representation of research being conducted. More randomized trials in children and adolescents, and more research in individuals during pregnancy and postpartum, are needed. Representation of minoritized racial and/or ethnic groups and in people of varying socioeconomic position is currently lacking.
2. Use clear, specific definitions for the intervention or exposure of interest and controls or comparators. The current body of evidence is highly inconsistent in the approaches used to categorize LNCSB intake and in the units used for such measurements.
3. When possible, examine if LNCSB are substituting, or not, for other beverages that contain energy.
4. Conduct more research examining the effects of specific types of low- and no-calorie sweeteners on growth, body composition, and risk of obesity outcomes.

Table 9 Evidence examining the relationship between LNCSB consumption in children and adolescents and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
Berkey, 2004^1^; PCS, Growing Up Today Study (GUTS), U.S.; Analytic N=11,634; Participant characteristics at baseline: children and adolescents; - Age: Range: 9–14y; - Female: 57%; - Race and/or Ethnicity: White: 95%; - SEP: NR; - Anthropometry: Overweight (>85th percentile CDC BMI charts): Boys: 23.2%; Girls: 17.5%;; Very lean (<10th percentile): Boys: 7.2%; Girls: 8.6%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Boys, Mean~2290 kcal/d; Girls, Mean~2050 kcal/d; Inclusion criteria: offspring of Nurses' Health Study II participants; ages 9–14 at baseline (1996); Exclusion criteria: any height >3 SD beyond gender-age-specific mean height (0.46% excluded); any 1-y height change which declined by >1 inch or increased by >3 SD above mean change (1.65% excluded); BMI < 12.0 kg/m2; BMI >3 SD above or below gender-age-specific mean (0.87% excluded); | Exposure: Diet soda; Other Exposures: Milk, 100% juice, SSB; Comparator: LNCSB intake (continuous); Exposure Assessment Methods and Timing:; Self-administered semi-quantitative, validated FFQ for older children and adolescents; Represents intake during previous year; - At baseline, 1y follow-up, 2y follow-up; Study beverage intake at baseline:; Boys: Mean~0.16 servings/d;; Girls: Mean ~0.18 servings/d; Outcomes Assessment Methods and Timing:; BMI from height and weight self-reported by children with measuring instructions and suggestion to ask someone for help provided (all have mothers who are nurses in NHSII); At baseline, 1y, & 2y follow-ups | [underlined: BMI change over 1y by 1 svg/d increase in diet soda intake], kg/m2, β (SE), Linear regression; Not adjusted for TEI; Boys: 0.119 (0.068), P=0.080; Girls: 0.065 (0.048), P=0.175; Adjusted for TEI; Boys: 0.100 (0.070), P=0.152; Girls: 0.056 (0.048), P=0.244; [underlined: BMI change over 1y per daily serving of diet soda], kg/m2, β (SE), Linear regression; Not adjusted for TEI; Boys: 0.116 (0.049), P=0.02; Girls: 0.051 (0.035), P=0.15; Adjusted for TEI; Boys: 0.116 (0.048), P=0.02; Girls: 0.051 (0.036), P=0.16 | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, physical activity; - Other: Tanner stage, menarche (girls), height growth, milk type (whole/2%/1%/nonfat/soy), inactivity, other beverage intake (sugar added, diet soda, fruit juices); Limitations:; - Did not account for key confounders: SEP, diet quality; - Differences in attrition (children lost to follow-up were older and had higher sugar added beverage intake and lower milk intake at baseline); self-reported outcome data; no preregistered data analysis plan; Funding:; NIH; Boston Obesity Nutrition Research Center Grant; CDC; Economic Research Service of the USDA; Kellogg’s
Blum, 2005^2^; PCS, U.S.; Analytic N=166; Participant characteristics at baseline:; Children; - Age: Mean (SD): 9.3 (1.0); Range: 3rd-5th grade; - Female: 55%; - Race and/or Ethnicity: White: 94%; - SEP: NR; - Anthropometry: BMI z-score, Mean=0.47, SD=1.0; Height, Mean=139.4 cm, SD=7.9; Weight, Mean=35.7 kg, SD=8.1; - Physical activity: NR; - Smoking: NR; - Diet quality: SSB intake, mean (SD): 7.4 (9.3) oz/d; - TEI: Mean=1957.7 kcal/d, SD=575.3; Inclusion criteria: children in grades 3–6; baseline and 2y measurements; Exclusion criteria: outlier values (>2.5 SD) on change in BMIz (n=2) | Exposure: Diet soda; Other Exposures: Milk, 100% juice, SSB; Comparator: LNSCB intake (continuous, oz/d); Exposure Assessment Methods and Timing:; 24-hr recall with two interviews per 24-hr period; parents of random sub-sample called to verify consumption at home; Represents intake during past 24-hr on a school day; Baseline, 2y; Study Beverage Intake at Baseline:; Mean (SD): 0.3 (1.8) oz/d; Outcomes Assessment Methods and Timing:; Weight and height measured by study staff. BMI z-score calculated (CDC age and gender specific) from height and weight; Overweight: BMIZ ≥1.0; Normal weight: BMIZ<1.0; Baseline, 2y | [underlined: BMI z-score], linear regression; Increase per oz/d increase in baseline intake:; P=NS, Data: NR; [underlined: Change in diet soda intake for change-in-BMIZ subgroups], oz/d; ANOVA, Mean (SD):; Unadjusted analysis; Within group differences (t-tests):; Normal wt at baseline & 2y, n=99: 1.1 (3.9), P<0.05; Overweight at baseline & 2y, n=48; 2.3 (7.3), P<0.05; Gained weight (Normal weight at baseline; Overweight at 2y), n=11: 3.6 (6.8), NS Lost weight (Overweight at baseline; Normal weight at 2y), n=6: 1.7 (4.1), NS Between group differences (ANOVA): All NS | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline; - Other: Baseline beverage intake; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, physical activity, diet quality; - Single 24-hr recall used to assess intake; impact of high level of missing data on analyses unclear; no preregistered analysis plan; Funding: NR
Davis, 2018^3^; PCS, Study of Latino Adolescents at Risk for Diabetes (SOLAR), U.S.; Analytic N=98; Participant characteristics at baseline:; Adolescents with overweight or obesity; - Age: Mean (SD): 14.0 (1.8) y; - Female: 44%; - Race and/or Ethnicity: 100% Hispanic; - SEP: NR; - Anthropometry: BMI % 96.6 (4.6); 17%; Overweight, 84% Obesity; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Mean: ~1800 kcal/d; Inclusion criteria: living in greater Los Angeles County area; 8–18y at baseline; BMI ≥85th percentile for age and sex; Hispanic ancestry (all four grandparents of Hispanic origin as determined by parental self-report); family history of type 2 diabetes; at least 2 annual visits, 1 year apart, with complete dietary and adiposity/metabolic data collected between 2004–2013; Exclusion criteria: taking any medication known to affect body composition or diagnosed with a disease known to affect body composition | Exposure: Artificial sweetened beverages (ASB, included those found in sodas, coffees, energy drinks, teas, sports drinks, juices, and flavored waters); 1 svg = 8 oz; Other Exposures:; Comparator: ASB intake (categorical): Control: No ASBs at baseline or 1yr; ASB initiators: No ASBs at baseline but started drinking ASBs at 1yr; Chronic ASB consumers: consumed ASBs at baseline and at 1yr; Exposure Assessment Methods and Timing:; Two 24hr dietary recalls using multiple pass method; Baseline, 1y; Study Beverage Intake at Baseline:; ASB initiators (14% of sample): 0 svg/d at baseline; Chronic ASB consumers (9% of sample): 1.4 (0.8) svg/d at baseline; Outcomes Assessment Methods and Timing:; Height measured using wall-mounted stadiometer; average of two measurements used for analysis; Weight measured using beam medical scale; average of two measurements used for analysis; BMI z-scores (BMIZ) determined using EPII 2000 software. Whole-body fat and soft lean tissue measured by DEXA; Baseline, 1y | [underlined: BMIZ], ANCOVA, Mean (SD),; Change at 1yr by ASB consumption:; Control (n=75): 2.0 (0.6); ASB Initiators (n=14): 2.1 (0.4); Chronic ASB (n=9): 2.2 (0.5); P for group effect = 0.15; P for interaction = 0.28; [underlined: Total fat], kg, ANCOVA, Mean (SD); Change at 1yr by ASB consumption: Control (n=75): 28.9 (10.7); ASB Initiators (n=14): 34.2 (10.2); Chronic ASB (n=9): 34.5 (12.2); P for group effect = 0.05; P for interaction = 0.96; [underlined: Trunk fat], kg, ANCOVA, Mean (SD); Change at 1yr by ASB consumption: Control (n=75): 15.1 (6.1); ASB Initiators (n=14): 17.2 (6.3); Chronic ASB (n=9): 17.0 (5.9); P for group effect = 0.22; P for interaction = 0.91; [underlined: Fat %,] ANCOVA, Mean (SD); Change at 1yr by ASB consumption:; Control (n=75): 34.4 (8.3); ASB Initiators (n=14): 37.0 (7.4); Chronic ASB (n=9): 35.5 (7.8); P for group effect = 0.34; P for interaction = 0.72 | Model Adjustments:; - TEI: yes; - Key confounders: sex, race and/or ethnicity; - Other: Tanner stage; Limitations:; - Did not account for key confounders: age, socioeconomic position, anthropometry at baseline, physical activity, diet quality; - No information on non-completers; No preregistered data analysis plan; LNCSB consumption was rare and may have affected power; Funding:; NIDDK; General Clinical Research Center for Health Resources
Dong, 2015^4^; PCS, Avon Longitudinal Study pf Parents and Children (ALSPAC), U.K.; Analytic N=4,646; Participant characteristics at baseline:; Children; - Age: Mean: 7.5y; - Female: 49%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean: 16.2; BMI z-score, Mean: 0.1; - Physical activity: Mean (SD): 22.9 min/d (15.4) (at age 11y); - Smoking: NR; - Diet quality: Mean (SD), g/d; Fruit: 80; Vegetables: 74; Whole grains: 12; - TEI: NR; Inclusion criteria: Complete dietary and anthropometric data at 7y, 10y, and 13y | Exposure: Diet soda (diet fizzy drinks, diet squashes and cordials); Other Exposures: Milk, SSB, 100% juice; Comparator: LNCSB (continuous; g/d): Per 100 g/d change over 3y, Per 100 g/d average across 3y; Exposure Assessment Methods and Timing:; Three-day food diary, child report with help from parent; Represents current intake; Ages 7y, 10y, 13y; Study Beverage Intake at Baseline:; Mean (SD): 133.3 (163.8) g/d; Outcomes Assessment Methods and Timing:; Height and weight measured by study personnel Calculated UK age and sex adjusted BMI z-score to represent adiposity. Excessive weight gain: increase in adiposity over 3y compared to reference group. BMI converted to g for interpretation (assumes 0.01 increase in BMI z-score = 50g); Ages 7y, 10y, 13y | [underlined: Excess weight gain (g) over 3y], per 100 g/d increase (change) or per 100 g/d intake (average), Mean, linear regression; Change: β: 10, P=NS; Average: β: 30, P=NS; Boys (n=2155); Change: β: 6, P=NS; Girls (n=2193); Change: β: 13, P=NS; 7–10y period; Change: β: 25, P=NS; 10–13y period; Change: β: 41, P=NS | Model Adjustments:; - TEI: no; - Key confounders: Sex, age, SEP (highest education level of child's mother), physical activity; - Other: Pubertal status (Tanner stage); Limitations:; - Did not account for key confounders: Race and/or ethnicity, anthropometry at baseline, diet quality; - No info on missing data; no preregistered data analysis plan; Funding: NR
Field, 2014^5^; PCS, Growing Up Today Study (GUTS) II cohort, U.S.; Analytic N=7,559; Participant characteristics at baseline:; Children and adolescents; - Age: Mean: ~13y (Range 9–16y); - Female: 55%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~20; Girls: 14.1% with overweight, 2.2% with obesity; Boys: 19.3% with overweight, 4.5% with obesity; - Physical activity: vigorous: ~7h/w; - Smoking: NR; - Diet quality: NR; - TEI: NR; Inclusion criteria: children of Nurse's Health Study II participants; age 9–15 at baseline; data on BMI from ≥2 consecutive questionnaires; Exclusion criteria: missing information on vigorous activity or reported >40h/wk vigorous activity; missing information on time spent watching TV, missing information on sports drink or diet soda consumption | Exposure: Low calorie soda, assessed as # cans/d but exact serving size is not specified; Other Exposures: SSB; Comparator: continuous; svg/d; Exposure Assessment Methods and Timing:; Youth/Adolescent questionnaire; validated; Baseline, 2y, 4y, 7y; Study Beverage Intake at Baseline: NR; Outcomes Assessment Methods and Timing:; Weight and height self-reported; BMI calculated as kg/m2; Baseline, 2y, 4y, 7y | [underlined: Change in BMI with baseline intake and change in intake], β (95% CI); [Note: change in intake was adjusted for baseline intake in these results. Analyses looking at only baseline intake or change in intake without adjusting for baseline are presented in the paper]; [underlined: Change in BMI with baseline intake and change in intake], β (95% CI); Girls:; Baseline intake: 0.21 (0.07, 0.35); Change in intake: 0.04 (−0.12, 0.20); Boys:; Baseline intake: 0.56 (0.32, 0.80); Change in intake: 0.45 (0.22, 0.69) | Model Adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, diet quality (SSB intake); - Other: Tanner stage of development (boys only), hours per day of television viewing, time between assessments, baseline and change values for other 2 beverages of interest; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position,; - High attrition and no information on non-completers; weight and height were self-reported; No preregistered data analysis plan; Funding:; Breast Cancer Research Foundation, NIH
Haines, 2007^6^; PCS, U.S.; Analytic N=2,516; Participant characteristics at baseline:; Adolescents; - Age: Mean (SD): Middle school cohort, 12.8 (0.8) y; High school cohort, 15.8 (0.8) y; Middle school cohort = 1/3 of participants; High school = 2/3; - Female: 55%; - Race and/or Ethnicity: Asian: 19.6%, Black: 18.9%, Hispanic: 5.8%, Native American: 3.6%, mixed race or other: 3.8%; white: 48.3%; - SEP: Low or low-middle SEP, 37%; - Anthropometry: BMI (Mean), Girls 22.4, Boys 22.5; Overweight (>85th percentile), Girls 25.7%, Boys 26.4%; - Physical activity: Moderate and vigorous physical activity, Mean (SD): Girls: 5.8 hr/wk (4.7);; Boys: 7.4 hr/wk (4.7); - Smoking: NR; - Diet quality: Fruits and vegetables, serv/d, Mean (SD); Girls: 4.2 (2.9); Boys: 3.8 (2.9); - TEI: Mean (SD), kcal/d:; Girls: 1,994 (1047);; Boys: 2,249 (1,216); Inclusion criteria: middle and high school students in 31 Minnesota schools beginning in 1998–1999 calendar year; completion of surveys for both Time 1 and Time 2; Exclusion criterion: missing survey at baseline or 5y | Exposure: Diet soda; Other Exposures: SSB, Dairy milk; Comparator: Diet soda (continuous; svg/d); Baseline intake, Change in intake; Exposure Assessment Methods and Timing:; 149 item semi-quantitative Youth and Adolescent FFQ (YAQ); Represents usual intake; Baseline, 5y follow up; Study Beverage Intake at Baseline:; Total LNCSB, Mean (SD); Girls: 0.2 (0.4) svg/d; Boys: 0.1 (0.4) svg/d; Outcomes Assessment Methods and Timing:; Weight and height self-reported; Overweight defined as BMI >85th percentile for age and gender, using Must et al. classification; Baseline, 5y follow up | [underlined: Overweight at 5y follow-up], OR (95% CI), Logistic Regression; Girls:; Baseline intake: 1.74 (1.13, 2.69); Change in intake: Data NR, P=NS; Boys:; Baseline intake: 1.58 (0.84, 2.99); Change in intake: Data NR, P<0.05; [underlined: Incident overweight], OR (95% CI), Logistic Regression; Girls:; Baseline intake: 1.99 (1.14, 3.50); Change in intake: Data NR, P=NS; Boys:; Baseline intake: 0.72 (0.21, 2.42); Change in intake: Data NR, P=NS | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, SEP (parental education level), anthropometry at baseline (baseline overweight status); - Other: Cohort; Limitations:; - Did not account for key confounders: Physical activity, diet quality; - No info on missing data; self-reported outcome data (height and weight); no preregistered data analysis plan; Funding:; Maternal and Child Health Bureau (HHS)
Hasnain, 2014^7^; PCS, Framingham Children's Study, U.S.; Analytic N=98; Participant characteristics at baseline:; Children; - Age: 3–5y; - Female: 55%; - Race and/or Ethnicity: Non-Hispanic White: 100%; - SEP: Maternal education >college, ~34%; 100% 2-parent household; - Anthropometry: BMI, Mean ~16.1 kg/m2; - Physical activity: Caltrac counts/hr, Mean: ~10.7; - Smoking: NR; - Diet quality: SSB (oz/d), Median (5th-95th %): 4.0 (0.0, 14.1); - TEI: Mean~1724 kcal/d; Inclusion criteria: 3rd- and 4th-generation descendants of original Framingham cohort; At least some dietary data age 3–9y and anthropometry data at 15–17y | Exposure: Unsweetened/diet beverages (diet/artificially sweetened carbonated and noncarbonated beverages, unsweetened and artificially sweetened tea and coffee); Other Exposures: Milk and milk alternatives, SSB, 100% juice; Comparator: Unsweetened/diet beverage intake (categorical; tertiles): T1 (Mean=0.0 oz/d, SD=0.0), T2 (Mean=0.4 oz/d, SD=0.2), T3 (Mean=2.3 oz/d, SD=1.5); Exposure Assessment Methods and Timing:; Up to 4 sets of 3-d diet records annually completed by parents (up to age 10y) or children (after age 10y); Represents usual intake; Baseline (3–5y), annually for 12y (age 15–17y). Intake patterns were similar from 3–5y and 6–9y, so these categories were collapsed for analyses.; Study Beverage Intake at Baseline: Unsweetened/diet beverages, Median (5th, 95th percentile): 0.0 oz/d (0.0, 3.3); Outcomes Assessment Methods and Timing:; Weight, height, waist circumference measured by study personnel; Four skinfolds (triceps, subscapular, suprailiac, abdominal) measured in duplicate following standard protocol Percent body fat measured with DXA scan (end of follow-up only); At baseline (3–5y), annually for 12y (age 15–17y) | [underlined: Effects of intake (by tertile) at ages 3–9y on outcomes at end of follow-up (ages 15–17y)]; linear regression; Body fat %, Mean: Data NR, P=0.5841; Sum of 4 skinfolds, mm: Data NR, P=0.2713; WC, cm: Data NR, P=0.3959; [underlined: Effects of intake (by tertiles) on sum of skinfolds over time]; mixed model; T1 vs T2: Data NR, P=0.2525; T1 vs T3: Data NR, P=0.0394; T2 vs T3: Data NR, P=0.3569; [underlined: Effects of intake (by tertile) at ages 3–9y on outcomes at end of follow-up (ages 15–17y)]; linear regression; BMI, kg/m2: Data NR, P=0.4444 | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, SEP (maternal education), anthropometry at baseline (baseline body fat), physical activity, diet quality (other beverages consumed); - Other: Percent of calories from fat, mean TV and video time, maternal BMI; Limitations:; - Exposure assessment validity unclear; no preregistered data analysis plan; Funding:; NHLBI; National Dairy Council
Johnson, 2007^8^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), Children in Focus (CIF) subsample, UK; Analytic N=5y & 9y (n=521); 7y & 9y (n=682); Participant characteristics at baseline: British children born to ALSPAC participants from 04/1991–12/1992.; - Age: Mean (SD): 5.16y (0.05); - Female: NR; - Race and/or Ethnicity: NR; - SEP: Maternal education and paternal class: Data NR; - Anthropometry: Fat mass at 5y, kg, Mean (SD): 8.47(4.98); Weight at 5y, kg, Mean (SD): 19.52 (2.54); Overweight at 5y (≥95th percentile): 15%; - Physical activity: NR; - Smoking: NA; - Alcohol intake: Dietary energy density, kJ/g at 5y: 8.52 (1.49); - TEI: TEI at 5y, Mean (SD) 6218 (1393) kJ/d; Misreporting of TEI, TEI / Estimated energy requirements (EER) at 5y, Mean (SD): 1.06 (0.24); Exclusion criteria: Missing data on diet or body composition | Exposure: Low energy beverages (reduced sugar or sugar-free fruit squashes, cordials, and diet fizzy drinks); Other Exposures: SSB, 100% juice, milk; Comparator: Different intake level of LNCSB (continuous, g/d or svg/d); Exposure Assessment Methods and Timing:; Parent-report, 3-day unweighed dietary records, previously validated using weighed dietary records; 5y, 7y; Study Beverage Intake at Baseline:; LNCSB intake, Median (IQR); 5y: 127 (0–311) g/d;; 7y: 140 (0–327) g/d; Paper contains beverage intake data at 5y and 7y stratified by maternal education; Outcomes Assessment Methods and Timing:; Fat mass (kg): DXA; Fat mass index (FMI): Fat mass (kg) / Height (m^5.8); log transformed; Height: valid measure by study staff; Weight: valid measure by study staff; Age: 9.8 (0.15)y | [underlined: Change in fat mass], kg/serving (95% CI), p-value, Linear regression; Change 5y-9y per serving of LNCSB at 5y (n=362): 0.26 (−0.004, 0.52), p=0.05; Change 7y-9y per serving of LNCSB at 7y (n=471): 0.26 (−0.12, 0.18), p=0.66; [underlined: Fat Mass Index quintile], Spearman correlation coefficient; By mean volume of LNCSB consumed (g/d) at age 5y: 0.21, P<0.0001; By mean volume of LNCSB consumed (g/d) at age 7y: 0.15, P<0.0001 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, socioeconomic position (maternal education, paternal class), anthropometry at baseline, physical activity, smoking, diet quality; - Other: TV watching, parental BMI, fat intake, fiber intake, EI/EER; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - High attrition/missing data; No information on non-completers; No preregistered data analysis plan; Funding:; U.K. Medical Research Council, the Wellcome Trust, and the University of Bristol
Kral, 2008^9^; PCS, U.S.; Analytic N=42; Participant characteristics at baseline:; Children; - Age: Mean: ~3y; - Female: 44%; - Race and/or Ethnicity: White: 100%; - SEP: NR; - Anthropometry: BMI z-score, Mean ~ −0.4; WC, Mean ~49.8 cm; - Physical activity: NR; - Smoking: NR; - Diet quality: SSB (oz/d), Mean (SEM); Low risk: 1.8 (1.0); High risk: 2.3 (1.0); - TEI: NR; Inclusion criteria: at either high or low risk of obesity based on maternal pre-pregnancy BMI; food records at ages 3, 4, 5, & 6y | Exposure: Diet soda (carbonated noncaloric beverages); Other Exposures: Milk, SSB, 100% juice; Comparator: Diet soda intake (change from 3y to 5y; continuous; kcal/d); Exposure Assessment Methods and Timing:; Three day weighed food and beverage record (2 weekdays, 1 weekend day) recorded by primary caregiver; Represents usual intake; Baseline, 1y & 2y follow ups; Study Beverage Intake at Baseline:; Mean ~0.03 oz/d; Outcomes Assessment Methods and Timing:; Waist circumference measured in triplicate at the narrowest part of torso by trained anthropometrists. Height and weight measured in triplicate by trained anthropometrists. BMI z-score calculated using CDC growth charts; Baseline, 1y, 2y, & 3y follow ups | [underlined: BMI z-score change from 5y – 6y], per change in kcal/d from 3y to 5y, β (SE), Linear mixed model:; Data NR, P>0.10; [underlined: WC change from 5y – 6y], Per change in kcal/d from 3y – 5y, β (SE), Linear mixed model:; Data NR, P=NS | Model Adjustments:; - TEI: yes; - Key confounders: age, race and/or ethnicity, anthropometry at baseline (change in BMIZ or WC from 3–5y), diet quality (though not adjusted for when TEI was added to the model); - Other: change in BMI z-score or waist circumference from ages 3 to 5 years; Limitations:; - Did not account for key confounders: sex, SEP, physical activity; - Study is underpowered; Baseline n NR and no information on non-completers; No preregistered data analysis plan; Exposure data based on parental weighed food records; Funding:; NIH; General Clinical Research Center; Nutrition Center of the Children’s Hospital of Philadelphia
Laska, 2012^10^; PCS, Identifying Determinants of Eating and Activity (IDEA) and Etiology of Childhood Obesity (ECHO), U.S.; Analytic N=535; Participant characteristics at baseline:; Adolescents; - Age: Mean: 14.6y; - Female: 51%; - Race and/or Ethnicity: ~85% White; - SEP: ~75% Parent college graduate; ~11% Eligible for free/reduced lunch; - Anthropometry: Mean BMI: 22.0 kg/m2; - Physical activity: Mean: ~310 min/d; - Smoking: NR; - Diet quality: Mean (SD); SSB, servings/d: Males: 1.02 (1.01); Females: 0.7 (0.84); Fast food, purchases/wk: Males: 0.91 (0.88); Females: 0.94 (1.2); Breakfast meals, days/wk: Males: 0.91 (0.2); Females: 0.88 (0.22); - TEI: Mean: 1982 kcal/d; Inclusion criteria: participants in 2 cohort studies (IDEA and ECHO); 6th through 11th grade at baseline; data from at least 2 time points; Exclusion criteria: < 1 day of accelerometry data; < 2d dietary recall data at baseline | Exposure: Diet soda (artificially sweetened soft drinks, fruit drinks, tea, coffee, and/or coffee substitutes); Diet or sugar-free soda or pop; Other Exposures: SSB; Comparator: Diet soda intake (continuous; svg/d); Exposure Assessment Methods and Timing:; Three 24hr recalls (self-report via telephone); represents 2 weekdays and 1 weekend day; Baseline, 2y; Study Beverage Intake at Baseline:; Mean (SD); Males: 0.16 (0.49) svg/d; Females: 0.18 (0.48) svg/d; Outcomes Assessment Methods and Timing:; Height measured without shoes using Shorr Height Board to nearest 0.1 cm; Weight (to nearest 0.1 kg) and percent body fat (%BF) assessed using digital bioelectrical impedance scale; Baseline, 2y | [underlined: %Body Fat], Change per svg/d increase of diet soda, β (SE), Linear regression; Males; TEI unadj: −0.22 (0.78), P=0.776; TEI adj: 0.09 (0.79), P=0.906; Females; TEI unadj: 0.54 (0.35), P=0.122; TEI adj: 0.55 (0.36), P=0.125; [underlined: BMI], kg/m2, Change per svg/d increase of diet soda, β (SE), Linear regression; Males; TEI unadj: −0.11 (0.24), P=0.660; TEI adj: −0.09 (0.24), P=0.722; Females; TEI unadj: 0.10 (0.23), P=0.683; TEI adj: 0.10 (0.23), P=0.674 | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age (grade in school), race and/or ethnicity, socioeconomic position (parent education, qualification for free/reduced price school lunch), anthropometry at baseline, physical activity; - Other: Puberty, study (ECHO vs. IDEA); Limitations:; - Did not account for key confounders: diet quality; - High attrition with no information on non-completers; No preregistered data analysis plan; Funding: NCI; NHLBI
Ludwig, 2001^11^; PCS, Planet Health intervention and evaluation project, U.S.; Analytic N=548; Participant characteristics at baseline:; Children and adolescents; - Age: Mean (SD): 11.7 (0.8) y; - Female: 48%; - Race and/or Ethnicity: 64% White, 15% Hispanic, 14% Afro-American, 8% Asian, 8% American Indian or other; - SEP: Median household income lower than that for all households in Massachusetts; - Anthropometry: BMI, mean (SD): 20.73 (3.99) kg/m2; 27% with obesity; - Physical activity: Activity ≥3.5 MET: 1.34 (1.09) hr/d; 38% Exercised to lose weight; - Smoking: NR; - Diet quality: SSB intake, mean (SD): 1.22 (1.10) servings/d; - TEI: Mean (SD): 8950 (4500) kJ/d; Inclusion criteria: control group of Planet Health intervention and evaluation project; residents of Boston area between 1995–1997; grade 6–7 at baseline; Exclusion criteria: changed schools at baseline; enrolled in special education classes; grades other than 6th or 7th; did not complete English-language version of questionnaire; implausible energy intake (≤2090 kJ/d or ≥29,260 kJ/d) | Exposure: Diet soda; Other Exposures: SSB, 100% juice baseline exposure data collected but associations with outcomes NR in this paper; Comparator: Diet soda intake (continuous; svg/d); Exposure Assessment Methods and Timing:; Youth food-frequency questionnaire (validated); intake assessed as frequency of consumption over past 30 days (never or < 1 can/mo, 1–3 cans/mo; 1 can/wk; 2–6 cans/wk; 1 can/d; ≥2 cans/d); Baseline, 19mo; Study Beverage Intake at Baseline: NR; Outcomes Assessment Methods and Timing:; Height measured to nearest 0.1 cm using a Shorr stadiometer; Weight measured to nearest 0.1 kg on a portable electronic scale; BMI calculated as kg/m2. Triceps-skinfold thickness measured twice by trained project staff with calibrated Holtain calipers. Obesity defined by a composite indicator of BMI and triceps skinfold thickness ≥85th% of age- and sex-specific reference data; Baseline, 19mo | [underlined: BMI], Linear regression, n=548 Change by diet soda svg/d at baseline: Negative β (Data NR), P=0.10; Change by increase in diet soda svg/d:; Negative β, Data NR, P=0.10; [underlined: Obesity], Logistic regression, n=398 Incidence by diet soda svg/d at baseline: Data NR, P=0.69; Incidence by increase in diet soda svg/d: OR=0.44, P=0.03 | Model Adjustments:; - TEI: yes and no; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline (BMI and triceps-skinfold thickness), physical activity; - Other: Percent energy from fat, energy-adjusted fruit juice intake, time spent watching television and videos (baseline and change over time) menarcheal status, indicator variables for schools; Limitations:; - Did not account for key confounders: socioeconomic position, diet quality; - No preregistered data analysis plan; Limited statistical power to detect associations with incident obesity (n=37 incident cases); Funding:; NIDDK; NICHD; CDC; Charles H. Hood Foundation
Macintyre, 2018^12^; PCS, Growing Up in Scotland (GUS), U.K. (Scotland); Analytic N=2,332; Participant characteristics at baseline:; Children; - Age: 4–5y; - Female: 49%; - Race and/or Ethnicity: NR; - SEP: Maternal education: 30% standard grades/intermediate vocational; 33% higher grades/upper vocational; 28% degree level academic/vocational qualifications; - Anthropometry: BMI: 74% "Healthy weight"; 16% with overweight; 11% with obesity; - Physical activity: 64% met physical activity guidelines (420 min/wk); - Smoking: NR; - Diet quality: Breakfast consumption:; ~95% usually eat breakfast; Fruit and vegetable consumption: ~70% ate <5 different types of fruits or vegetables in previous day; Sweets/crisps consumption:; ~45% eat sweets or crisps < every day of the week; Processed meals consumption:; ~23% had processed meal ≥2x in past 7; SSB consumption: 41% at least once/d; 14.7% 1–6x/wk; 44% <once/wk or never; - TEI: NR; Exclusion criteria: cases deemed to be "sensitive" (e.g., because of parental death); respondent not child's mother; missing data on exposure or outcome; respondent elected to skip physical activity questions because of child's longstanding illness or disability; outliers on BMI and television viewing; cases with no longitudinal weight (who had not responded at every sweep) | Exposure: Artificially sweetened beverage intake (ASB: diet or low calorie soft drinks, including cans, bottles, mixers, and diet or low-calorie flavored water; not including fresh fruit juice or water); Other Exposures: SSB; Comparator: LNCSB intake (categorical): Never or <1/wk (ref); 1–6 times/wk; ≥1/d; Exposure Assessment Methods and Timing:; Parent interview using single question on frequency of intake; Sweep 5 (age 4–5y); Study Beverage Intake at Baseline: Never or <1/wk: 61%; 1–6/wk: 14%; ≥1/d: 25%; Outcomes Assessment Methods and Timing:; Height and weight measured on non-carpeted surface by GUS project team following a protocol. BMI calculated as kg/m2. BMI classification defined according to British 1990 growth reference curves (Overweight: 85th% cutoff, Obesity: 95th% cutoff); At Sweep 4: (age 3–4y), and at ~3y follow-up (Sweep 7: age 7–8y) | [underlined: Overweight including Obesity at 7–8y], Logistic regression, OR (95% CI); <1/wk (ref) vs; 1–6 times/wk: 1.02 (0.71, 1.46), P=0.93; ≥1/d: 0.85 (0.63, 1.15), P=0.28; [underlined: Obesity at 7–8y], Logistic regression, OR (95% CI); <1/wk (ref) vs; 1–6 times/wk: 1.57 (1.05, 2.36), P=0.03; ≥1/d: 1.04 (0.74, 1.45), P=0.84; [underlined: BMI], kg/m2, Linear regression, β (95% CI); <1/wk (ref) vs; 1–6 times/wk: 0.30 (−0.01, 0.61), P=0.06; ≥1/d: −0.11 (−0.32, 0.11), P=0.34 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position (maternal education, household income), anthropometry at baseline, physical activity, diet quality (consumption of breakfast, fruit and vegetables, milk, water, sweets/crisps, and processed meals); - Other: Maternal age; mother’s BMI; television viewing on weekdays; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Start of follow-up and exposure do not coincide; Unclear if exposure assessment tool is validated; Exposure data only measured at baseline; High attrition with no information on non-completers; No preregistered data analysis plan; Funding:; Medical Research Council; Chief Scientist Office of the Scottish Government Directorates
Newby, 2004^13^; PCS, U.S.; Analytic N=1,345; Participant characteristics at baseline:; Low-income preschool children; - Age: Mean (SD): 2.9y (0.7); - Female: 50%; - Race and/or Ethnicity: Native American 11%, Other 6%, White 83%; - SEP: Maternal education, Mean~12.6y; Poverty level: <100%: 55%; 100–133%: 22%; >133–185%: 23%; - Anthropometry: BMI, Mean~16.6 kg/m2; At risk of overweight 14%, Overweight 6%; - Physical activity: NR; - Smoking: NR; - Diet quality: Soda intake: Mean~1.2 oz/d; ≥12 oz/d: ~3%; - TEI: Mean~1747 kcal/d; Inclusion criteria: children seen by North Dakota WIC Program between 1/1/95 and 6/30/98; Exclusion criteria: only 1 clinic visit, underweight (based on age- and sex-specific 5th percentile BMI), implausible energy intake (<800 kcal or >3500 kcal/d), unreasonable measures for weight-for height, weight-for-age or height-for-age, "suspicious" change in BMI between visits (< −4 or >4 kg/m2), child breastfeeding at baseline | Exposure: Diet soda intake (included any no- or low-calorie soda); Other Exposures: Milk, SSB, 100% juice; Comparator: Diet soda intake (continuous; oz/d); Exposure Assessment Methods and Timing:; Validated FFQ; represents dietary intake during previous month; At baseline, follow-up 6–12mo later (mean 8.4mo); Study Beverage Intake at Baseline:; Mean~0.7 oz/d; ≥12 oz/d: ~3%; Outcomes Assessment Methods and Timing:; Height measured by trained staff using wall-mounted measuring board. Weight measured by trained staff using standard floor-model beam scale. Age- and sex-specific BMI calculated based on 2000 CDC growth charts. At risk of overweight (BMI 85th to <95th percentile); Overweight (BMI≥95th percentile); At baseline, follow-up 6–12mo later (mean 8.4mo) | Change per oz/d increase, β (SE), linear regression; [underlined: Weight]; TEI adj: 0.01 (0.02), P=0.92; [underlined: BMI]; TEI adj: 0.01 (0.02), P=0.83; Estimates remained similar when TEI was omitted from model. (Data NR) | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, SEP (maternal years of education, poverty level), anthropometry at baseline (weight), diet quality (other beverages); - Other: Birth weight, change in height, residence (town or city, rural, reservation, military base); Limitations:; - Did not account for key confounders: Physical activity; - No preregistered data analysis plan; Funding:; USDA; NIH Health Harvard Education Program in Cancer Prevention Control; Boston Obesity Nutrition Research Center
Striegel-Moore, 2006^14^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,371; Participant characteristics at baseline:; Children; - Age: Mean ~10y; - Female: 100%; - Race and/or Ethnicity: Black 51%, White 49%; - SEP: SEP: <$10K: 17%; $10<20K: 14%; $20<30K: 15%; $30<40K: 14%; $40<50K: 12%; $50<75K: 17%; ≥$75K: 6%; - Anthropometry: Weight: ~ 37kg; Height: ~141 cm; - Physical activity: NR; - Smoking: NR; - Diet quality: Soda intake, g/d, Mean (SE): White, 135.45 (8.29); Black, 134.53 (7.85); - TEI: NR; Inclusion criteria: girls age 9 or 10 at study entry who identified themselves as "Black" or "white", non-Hispanic, with racially concordant parents or guardians | Exposure: Diet soda intake (artificially sweetened carbonated soft drinks, diet or low calorie); Other Exposures: Milk, SSB, 100% juice, Coffee/tea; Comparator: Diet soda intake (continuous; 100 g/d); Exposure Assessment Methods and Timing:; Validated 3-d food records; represents usual intake over 3 consecutive days (2 weekdays and 1 weekend day); At baseline, and annually for years 1–5, then at years 7, 8, 10; Study Beverage Intake at Baseline:; Mean (SE), g/d: White, 22.36 (4.52); Black, 7.20 (1.75); Outcomes Assessment Methods and Timing:; Weight measured twice by research staff using electronic scale. Height measured twice by research staff using stadiometer. BMI calculated as weight in kilograms divided by height in meters squared; Baseline, annually until 10y follow-up | [underlined: BMI], Linear regression; Change per 100g/d increase: β: −0.010, SE: 0.013, P>0.05 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, diet quality (other beverages); - Other: Study site; Limitations:; - Did not account for key confounders: SEP, anthropometry at baseline, physical activity; - No preregistered data analysis plan; Funding: NHLBI
Vanselow, 2009^15^; PCS, Project EAT, U.S.; Analytic N=2,294; Participant characteristics at baseline:; Adolescents; - Age: 14.9y; - Female: 55%; - Race and/or Ethnicity: 62.9% white, 17.9% Asian American, 9.7% African American, 3.9% Hispanic, 2.7% American Indian, 2.9% mixed/other; - SEP: Parent education level (highest), %, chi-square test: *unclear what "highest" means: ~18%; - Anthropometry: NR; - Physical activity: Strenuous exercise, hr/wk, mean (SE), chi-square test 0 svg/wk: 3.9 (0.0); 0.5–6 servings/wk: 3.9 (0.1); ≥7 svg/wk: 3.5 (0.1); P<0.05; - Smoking: NR; - Diet quality: Saturated fat, mean ~10.2% kcal; Fiber, ~8.0 g/1000 kcal; Calcium: mean ~560 mg/d; Soft drinks (n=2178, 5% missing data): 11.1% 0 svg/wk, 60.8% 0.5–6 svg/wk, 28.1% ≥7 svg/wk; Punch (n=2170, 5.4% missing data): 14.4% 0 svg/wk, 67.1% 0.5–6 svg/wk, 18.5% ≥7 svg/wk; - TEI: mean ~2100 kcal/d; Exclusion criteria: lost to follow-up, missing exposure or outcome data, implausible energy intakes | Exposure: Low-calorie soft drinks. Serving size NR.; Other Exposures: SSBs, dairy milk, 100% juice; Comparator: Different intake of low-calorie soft drinks, categorical intake (0, 0.5–6, ≥7 servings/wk); Exposure Assessment Methods and Timing:; Validated 149-item youth and adolescent food-frequency questionnaire (YAQ).; Responses ranged from “never/less than once per month” to ≥4 glasses, cups, cans, or drinks per day depending on beverage type.; 1998–1999, 2003–2004; Study Beverage Intake at Baseline:; (n=2180, 5% missing data): 64.6% 0 servings/wk, 29.2% 0.5–6 servings/wk, 6.2% ≥7 servings/wk; Outcomes Assessment Methods and Timing:; BMI calculated from self-reported height and weight. Overweight considered as BMI ≥85th percentile for sex and age; 1998–1999, 2003–2004 | [underlined: Change in BMI over 5y] by number of servings/wk of time 2 LNCSB intake, kg/m2, mean (SE), multivariable linear regression; Model 3, adjusted for dieting variables 0 servings/wk: 1.80 (0.09); 0.5–6 servings/wk: 2.15 (0.15); ≥7 servings/wk: 1.81 (0.29); P=0.13 | Model Adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity (models 2 and 3), diet quality (SSB intake, models 2 and 3); - Other: Model 3: soft drinks, low-calorie soft drinks and white milk assessed together in the model; adjusted for key confounders; baseline white milk, soft drink, and low-calorie drink consumption, baseline and time 2 strenuous physical activity, time 2 weekday television watching and coffee and tea consumption, and dieting and parental weight-related concerns; Limitations:; - No preregistered data analysis plan; No information on non-completers; Lack of accurate assessment of exposure portion sizes; Funding:; HHS (Maternal and Child Health Bureau, Health Resources and Services Administration)
Zheng, 2015(a)^16^; PCS, Childhood Asthma Prevention Study (RCT), Australia; Analytic N=158; Participant characteristics at baseline:; Children; - Age: Mean: ~8y; - Female: 48%; - Race and/or Ethnicity: Mother born in Australia/New Zealand ~78%; Father born in Australia/New Zealand ~73%; - SEP: Maternal education level >12y ~55%; Paternal education level >12y ~58%; Living in disadvantaged area ~20%; - Anthropometry: BMI z-score, Mean (SD): 0.4(1.0); Overweight/obesity: 27.2%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Mean ~8.0 MJ/d (~1,912 kcal/d); Inclusion criteria: participants in CAPS RCT; participation in anthropometric assessment at 8y and dietary assessment at age 9y; Exclusion criteria: incomplete diet data, misreporting of energy intake, missing anthropometric data | Exposure: Diet drink intake (low energy drinks sweetened with artificial sweeteners); Other Exposures: Milk, SSB, 100% juice; Comparator: Diet drink intake (continuous; 100 g/d); Exposure Assessment Methods and Timing:; Three 24-hr dietary recalls via phone using multiple pass approach completed by children with parental assistance; Represents usual dietary intake on nonconsecutive weekdays and weekends; At 1y follow-up (age 9y); Study Beverage Intake at Baseline:; Mean (SD): ~90(89) g/d; Outcomes Assessment Methods and Timing:; Weight measured to nearest 0.1kg. Height measured using stadiometer. Age- and sex-specific BMI z-scores (BMIZ) calculated using 2000 CDC growth charts. Percentage body fat measured by bioimpedance analysis.; Baseline (age 8y), and 3.5y follow-up (age 11.5y) | [underlined: BMIZ], Change per 100 g/d increase, β (SE), Linear regression; TEI unadj: −0.18 (0.007), P=0.02; TEI adj: −0.20 (0.07), P=0.01; [underlined: % Body Fat], Change per 100 g/d increase, β (SE), Linear regression; TEI unadj: −1.23 (0.70), P=0.09; TEI adj: −1.41 (0.70), P=0.046 | Model Adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP (socioeconomic index for area score, parental education level), anthropometry at baseline (BMI-Z); - Other: Maternal age at birth, presence of gestational diabetes, exclusive breastfeeding at 3mo, pubertal status, randomization group (omega-3 fatty acid dietary supplementation and house dust mite reduction); Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity, diet quality; - Exposure measured at baseline only; Baseline data for exposure and outcome occurred 1 year apart; Funding:; National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead
Zheng, 2015(b)^17^; PCS, Healthy Start Study (RCT), Denmark; Analytic N=352; Participant characteristics at baseline:; Children; - Age: Mean (SD): 4.1y (1.1); - Female: 45%; - Race and/or Ethnicity: NR; - SEP: Maternal education level, Tertiary or above: 78.0%; Paternal education level, Tertiary or above: 61.0%; Parents divorced 5.6%; - Anthropometry: Body weight (kg), Mean (SD): 18.0 (3.3); BMI z-score: 0.3 (0.9); - Physical activity: High: 59.2%; - Smoking: NR; - Diet quality: SSB, g/d, Mean (SD): 92 (107); - TEI: Mean (SD): 4.97mJ/d (0.95) (~1,195 kcal/d); Inclusion criteria: participants in RCT designed to prevent overweight and obesity among 2–6y Danish children who were normal weight but had high predisposition for future overweight (present study includes children from both intervention and control groups who participated in both baseline and follow-up exams over 1.5y);; Exclusion criteria: misreported energy intake, incomplete diet data | Exposure: Diet drink intake (artificially-sweetened beverages); Other Exposures: SSB, milk; Comparator: Diet drink intake (continuous; 100 g/d); Exposure Assessment Methods and Timing:; 4-d dietary record completed by parents; represents dietary intake on both weekdays and weekends; Baseline, 1.5y follow up; Study Beverage Intake at Baseline:; Mean (SD): 24.8 (65.0) g/d; Outcomes Assessment Methods and Timing:; Height measured using stature meter; Weight measured using mechanical weight or beam-scale. Age- and sex-specific BMIZ calculated using Lambda-Mu-Sigma method; Baseline, 1.5y follow up | Nutrient Residual Model (includes beverage intake residuals and total energy intake); Linear regression, Change per 100 g/d increase:; [underlined: BMIZ]; β: −0.02, SE: 0.02, P=0.41; [underlined: Body weight]; β: −0.07, SE: 0.05, P=0.13; Energy Partition Model (includes absolute amount of individual beverage intake and energy from non-beverage sources); Linear regression, Change per 100 g/d increase:; [underlined: BMIZ]; β: −0.01, SE: 0.02, P=0.66; [underlined: Body weight]:; β: −0.07, SE: 0.04, P=0.20 | Model Adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP, anthropometry at baseline, physical activity, diet quality (other beverages); - Other: Intervention allocation, parents divorced, number of siblings living with the child, maternal pre-pregnancy overweight; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No information on non-completers; No preregistered data analysis plan; Funding:; No funding received

a Abbreviations: ANOVA: analysis of variance; ANCOVA: analysis of covariance; ASB: artificial/artificially sweetened beverage; BMI: body mass index; BMIZ: BMI z-score; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; d: day; DEXA/DXA: dual energy x-ray absorptiometry; EER: estimated energy requirement; EI: energy intake; FFQ: food frequency questionnaire; fl oz: fluid ounces; g: grams; HHS: Department of Health and Human Services; kg: kilogram; kJ: kilojoules; LNCSB: low- and no-calorie sweetened beverages; M: meter; mL: milliliter; mo: month; NCI: National Cancer Institute; NHLBI: National Heart, Lung, and Blood Institute; NHS II: Nurses Health Study II; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NR: not reported; NS: not significant; OR: odds ratio; Oz: ounce; PCS: prospective cohort study; RCT: randomized controlled trial; Ref: reference; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SSB: sugar sweetened beverages; svg: serving; TEI: total energy intake; USDA: United States Department of Agriculture; WC: waist circumference; wk: week; wt: weight; y: year(s)

Table 10 Risk of bias for observational studies examining LNCSB consumption in children and adolescents and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Berkey, 2004 ^1^ | HIGH | LOW | LOW | LOW | HIGH | SOME CONCERNS | HIGH | HIGH
Blum, 2005 ^2^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Davis, 2018 ^3^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dong, 2015 ^4^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Field, 2014 ^5^ | HIGH | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Haines, 2007 ^6^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Hasnain, 2014 ^7^ | LOW | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Johnson, 2007 ^8^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kral, 2008 ^9^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Laska, 2012 ^10^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ludwig, 2001 ^11^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Macintyre, 2018 ^12^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Newby, 2004 ^13^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Striegel-Moore, 2006 ^14^ | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Vanselow, 2009 ^15^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Zheng, 2015(a) ^16^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zheng, 2015(b) ^17^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 11 Evidence examining the relationship between LNCSB consumption in adults and body composition and risk of obesity^b^

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
Bonnet, 2018^20^; RCT-Crossover, ‘Comparison of the Effects of a 12-Week Consumption of Two Carbonated Beverages on Insulin Sensitivity’ (SEDULC), France; Baseline N=60, Analytic N=50 (Attrition: 17%); Power: To demonstrate non-inferiority between 2 beverages for main outcome (insulin sensitivity) with a type I error of 5% and a type II error of 20%, an estimated minimum of 22 individuals were needed for the analysis; Participant characteristics at baseline: Adults; - Age: Mean (SD): 31.1 (10.3)y; - Female: 56%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: BMI, mean (SD): 24.7 (3.2) kg/m2; WC, mean (SD): 82.6 (8.6) cm; - Physical activity: NR; - Smoking: NR; - Diet quality: Simple sugar intake: ~125 g/d; - TEI: ~2645 kcal/d; Inclusion criteria: healthy men and women with normal wt or overweight; not regular users of high-intensity sweeteners (consuming ≥1 can of beverage with high-intensity sweeteners or 1 spoonful of high-intensity sweeteners/wk (or its equivalent from foods)).; Exclusion criteria: acute illness, past or present intestinal disease or kidney disease, history of diabetes or bariatric surgery, treatment that could interfere with glucose homeostasis, abnormal thyroid hormone levels, elevated liver markers, consumed >3–4 glasses of alcoholic drinks/d (>36 g of ethanol), or were pregnant or lactating | Intervention: High-intensity sweetener beverage (HISB): carbonated water containing aspartame and acesulfame K (2 cans of 330 mL/d), n=50; Comparator: Unsweetened beverage (UB): carbonated water (2 cans of 330 mL/d), n=50; Study beverage intake at baseline: HISB: <1 can (inclusion criterion); Duration: 12wk each arm, with 4wk washout period between arms (12wk+ 4wk wash-out +12wk=28wk); Compliance: NR; Outcomes Assessment Methods and Timing:; Weight and waist size were measured at assessment visit (methods NR); Baseline, 12wk follow-up (start and end of each study arm) | [underlined: Waist circumference], cm, Mean (SE), per protocol; Change over time, within group: 0wk, 12wk; UB: 82.45 (1.1), 82.70 (0.6); HISB: 82.47 (1.1), 82.90 (0.7); Change over 12wk between groups:; UB: 0.76 (0.6); HISB: 0.96 (0.7); P=0.84; [underlined: Weight], kg, Mean (SE), per protocol; Change over time, within group: 0wk, 12wk; UB: 73.99 (1.4), 74.02 (0.4); HISB: 74.65 (1.4), 73.43 (0.4); Change over 12wk between groups:; UB: 0.34 (0.4); HISB: −0.25 (0.4); P=0.26; [underlined: BMI], kg/m^2^, Mean (SE), per protocol; Change over time, within group: 0wk, 12wk “BMI remained stable over each intervention period without differences between the periods”, Data NR, P=NS; Change over 12wk between groups: Data NR, P=NS | Model adjustments:; - TEI: no; - Other: Sequence; Limitations:; - Methods for randomization and concealment NR; Compliance measures not reported; Differences in attrition; Power not based on these outcomes (may be underpowered); Trial registry did not include data analysis plan; registry does not contain these outcomes as primary or secondary outcomes; Funding:; Institute for European Expertise in Physiology (Paris, France); The Coca-Cola Company (USA)
Madjd, 2015^32^; RCT-Parallel, Iran; Baseline N=71, Analytic N=62 (Attrition: 13%); Power: Final sample size of 56 for diff 2.0±2.5 kg in weight loss, α=0.05, β=85%; Participant characteristics at baseline: Adult women attending a weight loss clinic; - Age: ~32y; - Female: 100%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: BMI ~33.7 kg/m2; - Physical activity: NR; - Smoking: 100% nonsmokers; - Diet quality: NR; - TEI: ~2447 kcal/d; Inclusion criteria: women aged 18–50y, BMI 27–40 kg/m^2^, self-reported habitual consumers of diet beverages willing to introduce a dietary change to lose weight that might include changing beverage consumption, nonsmokers, free of established cardiovascular diseases, stroke, diabetes, liver diseases, kidney diseases, depression, cancer, or autoimmune disease; ability to keep an adequate 4-d food record and readiness to participate in daily physical activity; Exclusion criteria: pregnancy or lactation during the previous 6mo or planned pregnancy in the next 6mo, weight loss ≥10% of body weight within 6mo before study enrollment, participating in a research project involving weight loss or physical activity in previous 6mo, taking medication to lower lipids/cholesterol or that could affect metabolism or change body weight; self-report of heart disorders, frequent chest pains, or faintness or dizziness on the Physical Activity Readiness Questionnaire | Intervention: DB, 1/d, 250 mL after lunch, 5d/wk; drink water remainder of week; provided with beverages; n=32/36; Other interventions: All participants: Phase 1 (24wk): weight loss phase: started a hypoenergetic diet (500–1000kcal deficit based on EER) according to NovinDiet protocol, which included advice to gradually increase activity levels to achieve 60 min of moderate activity 5d/wk; Phase 2 (53wk): weight maintenance phase: monthly group and individual sessions with dietitian; Study beverage intake at baseline: Habitual consumers of DB (inclusion criteria); Comparator: Replaced regular consumption of diet bevs with water; drank 250 mL water after lunch; n=30/35; Duration: 24wk; Compliance: NR; Outcomes Assessment Methods and Timing:; Weight measured by a dietitian using a digital calibrated scale. Height measured by a dietitian using a wall-mounted stadiometer. BMI calculated as kg/m2. Waist circumference (WC) measured by dietitian with measuring tape at smallest horizontal circumference between ribs and iliac crest; Baseline, 12wk, 24wk | [underlined: WC], cm, Mean (SD), per protocol; Change within group: 0wk, 24wk Water: 104.9 (5.9), 96.3 (5.7), P<0.001; DB: 103.7 (6.2), 95.8 (6.7), P<0.001; Change over time, between groups:; Water: −8.6 (3.4); DB: −7.9 (2.7); Group*time, 2-factor ANOVA, P=0.354; [underlined: Weight], kg, Mean (SD), per protocol; Change within group: 0wk, 24wk; Water: 88.7 (8.9), 79.9 (8.3), P<0.001; DB: 87.9 (9.9), 80.3 (10.2), P<0.001; Change over time, between groups:; Water: −8.8 (1.9); DB: −7.6 (2.1); Group*time, 2-factor ANOVA, P=0.015; [underlined: BMI], kg/m2, Mean (SD), per protocol; Change within group: 0wk, 24wk; Water: 33.9 (3), 30.6 (2.8), P<0.001; DB: 33.5 (3.6), 30.6 (3.8), P<0.001; Change over time, between groups:; Water: −3.4 (0.7); DB: −2.9 (0.8); Group*time, 2-factor ANOVA, P=0.002 | Model adjustments:; - TEI: no; - Other: NS at baseline: fat intake, carbohydrate intake, marital status, cholesterol (total, HDL, LDL), triglycerides, fasting plasma glucose, HbA1c, insulin, HOMA-IR; Limitations:; - No measure of compliance; Trial registry did not include data analysis plan; Funding:; School of Life Sciences, University of Nottingham, United Kingdom; Digestive Disease Research Institute affiliated with Tehran University of Medical Sciences
Madjd, 2018^33^; RCT-Parallel, Iran; Baseline N=71, Analytic N=56 (Attrition: 21%); Power: With the assumption of a detectable difference in weight loss of 2.5 kg at 18 months and an SD= 3 kg, 51 participants were required to achieve 85% power of detecting a treatment effect (two-sided significance level of 5%); Participant characteristics at baseline: Adult women attending a weight loss clinic; - Age: ~32y; - Female: 100%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: BMI ~33.7 kg/m2; - Physical activity: NR; - Smoking: 100% nonsmokers; - Diet quality: NR; - TEI: ~2447 kcal/d; Study beverage intake at baseline: Habitual consumers of DB (inclusion criteria); Inclusion criteria: women aged 18–50y, BMI 27–40 kg/m2, self-reported habitual consumers of DBs, nonsmokers, free of established cardiovascular diseases, stroke, diabetes, liver diseases, kidney diseases, depression, cancer, or autoimmune disease; ability to keep an adequate 4-d food record and readiness to safely participate in daily physical activity.; Exclusion criteria: pregnancy or lactation during the previous 6 mo or planned pregnancy in the next 6 mo, weight loss ≥10% of body weight within 6 mo before enrollment in study, participating in a research project involving weight loss or physical activity in previous 6 mo, taking medication to lower lipids/cholesterol or that could affect metabolism or change body weight; self-report of heart disorders, frequent chest pains, or faintness or dizziness on the Physical Activity Readiness Questionnaire | Intervention: Diet beverage, 1/d, 250 mL after lunch, 5d/wk; drink water remainder of week; provided with beverages; n=29/36; Other interventions: All participants started a hypoenergetic diet (500–1000kcal deficit based on EER) according to NovinDiet protocol, which included advice to gradually increase activity levels to achieve 60 min of moderate activity 5d/wk; Comparator: replaced regular consumption of diet bevs with water; drank 250 mL water after lunch; n=27/35; Duration: 24wk; Compliance: NR; Outcomes Assessment Methods and Timing:; Weight measured by a dietitian using a digital calibrated scale. Height measured by a dietitian using a wall-mounted stadiometer.; BMI calculated as kg/m2. Waist circumference (WC) measured by dietitian with a rigid measuring tape at smallest horizontal circumference between ribs and iliac crest; Baseline, 24wk, 77wk follow-up | [underlined: WC], cm, Mean (SD), ITT, multiple imputations with linear regression; Change within group: 24wk, 77wk; Water: 106 (5.8), 96 (5.6), 94.3 (3.9), P<0.001; DB: 103.5 (5.9), 95.8 (6.7), 94.5 (4.7), P<0.001; Change over 12mo, between groups,; ANCOVA:; Water: −2.1 (3.1); DB: −1.2 (3.2) P=0.188; Change over 18mo, between groups, 2- factor ANOVA:; Group*time, P=0.286; [underlined: Weight], kg, Mean (SD), ITT, multiple imputations with linear regression; Change within group: 0wk, 24wk, 77wk; Water: 88.2 (8.8), 79.7 (7.9), 78 (6.1), P=NS; DB: 87.6 (9.8), 80 (9.7), 79.8 (8.2), P=NS; Change over 12mo, between groups,; ANCOVA:; Water: −1.7 (2.8); DB: −0.1 (2.7); P=0.001; Change over 18mo, between groups, 2- factor ANOVA:; Group*time, P=0.005; [underlined: BMI], kg/m2, Mean (SD), ITT, multiple imputations with linear regression; Change within group: 0wk, 24wk, 77wk; Water: 33.9 (3), 30.6 (2.7), 30 (2.3), P=NS; DB: 33.5 (3.6), 30.6 (3.5), 30.5 (2.9), P=NS; Change over 12mo, between groups, ITT, ANCOVA:; Water: −0.7 (1.0); DB: −0.05 (1.1); P=0.003; Change over 18mo, between groups, 2- factor ANOVA:; Group*time, P=0.005 | Model adjustments:; - TEI: no; - Other: NS at baseline: fat intake, marital status, cholesterol (total, HDL, LDL), triglycerides, fasting plasma glucose, HbA1c, insulin, HOMA-IR; Limitations:; - No measure of compliance; Trial registry did not include data analysis plan; Funding:; School of Life Sciences, University of Nottingham, United Kingdom; Digestive Disease Research Institute affiliated with Tehran University of Medical Sciences
Maersk, 2012^34^; RCT-Parallel, Denmark; Baseline N=60, Analytic N=47 (Attrition: 22%); Power: NR; Participant characteristics at baseline: adults with overweight and obesity; - Age: ~39y (Range 20–50y); - Female: 64%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~32 kg/m2 (Range 26–40); - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Inclusion criteria: healthy, nondiabetic participants with a BMI between 26–40 kg/m2, age 20–50y, blood pressure <160/100 mmHg | Intervention: Aspartame-sweetened diet cola (Coca Colas; 1 L/d), n=12; Other interventions: sucrose-sweetened soft drink, skim milk; Comparator: Still mineral water (Aqua d’or; 1 L/d), n=13; Study beverage intake at baseline: NR; Duration: 6mo; Compliance: Empty bottles or cartons every 3–4wk; 7-d dietary records at baseline, 3mo, 6mo; compliance NR; Outcomes Assessment Methods and Timing:; Weight: method NR; Total fat mass and lean body mass determined by DXA; At baseline, 6mo follow-up | [underlined: Total fat mass], kg, ANOVA, Mean (SE) Percent change over time, between groups:; Water: 0.490 (2.6); Diet Cola: −0.52 (2.5); [underlined: Lean mass], kg, ANOVA, Mean (SE) Percent change over time, between groups:; Water: −0.189 (0.8); Diet Cola: 0.951 (0.8); Data are also provided on subcutaneous abdominal adipose tissue (SAAT), visceral adipose tissue (VAT), and the ratio of the two; none were significant for the exposures of interest.; [underlined: Weight], kg, ANOVA, Mean (SE) Percent change over time, between groups:; Water: 0.576 (1.0); Diet Cola: 0.114 (1.1) | Model adjustments:; - TEI: yes (between-group differences NS at baseline or during study); Limitations:; - Baseline differences in VAT, skeletal muscle fat, and liver fat between groups; Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; The Food Study Group/Danish Ministry of Food, Agriculture and Fisheries; Novo Nordic Foundation; Clinical Institute at Aarhus University, Denmark; Danish Dairy Company, Arla Foods
Peters, 2014^38^; RCT-Parallel, U.S.; Baseline N=303, Analytic N=279 (Attrition: 8%); Power: Assuming the true difference was 0.73 kg (1/3 of the equivalence margin) and common SD of 4.2 kg, a sample size of 63 per arm was required using two, one-sided t-tests to ensure at least 80% power with an alpha level of P< 0.05 to establish equivalence; Participant characteristics at baseline: Adults with overweight or obesity at baseline; - Age: ~48y; - Female: 82%; - Race and/or Ethnicity: ~62% White, ~28% Black/African American, <1% Asian or Pacific Islander, AI/AN, Multiracial; 11% Hispanic/Latino; - SEP: NR; - Anthropometry: Mean body weight: ~94kg; Mean BMI ~33.5 kg/m2; - Physical activity: No more than 300 minutes/wk (inclusion criterion); - Smoking: NR; - Diet quality: NR; - TEI: NR; Inclusion criteria: age 21–65y; BMI 27–40 kg/m2; weight stable within 10 lb during past 6 mo; no more than 300 min of physical activity weekly; drinking non-nutritive sweetener (NNS) beverages at least 3 times/wk; willing to discontinue NNS beverages if randomized to water group; physician approval stating that they were in good general health; Exclusion criteria: women who were lactating or pregnant during previous 6mo or planning on becoming pregnant; diabetes, CVD, uncontrolled hypertension, other diseases potentially interfering with weight loss, e.g., gastrointestinal or thyroid disease) or who used medications affecting weight and metabolism | Intervention: NNS group, n=158: asked to consume ≥24 fl oz/d (710 mL) of NNS beverages for 1y, with unrestricted water consumption. Premixed beverages containing NNS and <5 kcal/8-oz serving (237 ml) qualified as NNS beverages; Other interventions: All participants: 12wk weight loss phase: weekly, 60-min instructional classes from weight loss intervention; Individual energy targets for weight loss equal to each participant’s estimated resting metabolic rate (RMR), Energy targets were adjusted, as needed, to attempt weight loss of 1 to 2 pounds/wk; Participants given coupons redeemable for a monthly supply of NNS beverages or bottled water; Study beverage intake at baseline: Included: drink NNS bevs 3/wk; Comparator: Water group, n=150: asked to consume ≥24 fl oz/d (710 mL) of water for 1y and refrain from NNS beverage consumption. Instructed to not add NNS to beverages such as coffee/tea; permitted to consume foods with NNS, although not instructed to do so; Duration: 12 wk; Compliance: Participants asked to record daily beverage intake using paper logs; compliance was 98.1% (NNS) and 97.8% (water); Outcomes Assessment Methods and Timing:; Height measured with stadiometer; Weight measured on a digital scale. Waist circumference (WC) measured at top of iliac crest, based on 2 consecutive measures Baseline, 12wk | [underlined: WC at 12wks], cm, Mean (SD), ITT, compound symmetry model; Over time, within group: Baseline, 12 wk, change; Water: 107.10 (0.87), 102.74 (0.90), −4.36 (0.50) cm, P<0.0001; NNS: 108.00 (0.86), 102.27 (0.88), −5.73 (0.49) cm, P<0.0001; Change between groups (NNS - water): −1.36 (0.70) P=0.0528; [underlined: Weight loss at 12wks], kg, Mean (SD), ITT, Satterthwaite two sample t test; Over time, within group: Baseline, 12 wk, change; Water: 93.15 (12.94); 89.06 (12.86), −4.09 (3.74) kg, P<0.0001; NNS: 93.91 (13.46); 87.97 (13.39), −5.95 (3.94) kg, P<0.0001; Change between groups (NNS - water): −1.85 (3.84) kg, P<0.0001; [underlined: % Achieved 5% weight loss], ITT, Chi-squared analysis; Water (n=149): 43.0%; NNS (n=154): 64.3%, P=0.0002 | Model adjustments:; - TEI: no; Limitations:; - Allocation and concealment NR; Funding:; American Beverage Association
Peters, 2016^39^; RCT-Parallel, U.S.; Baseline N=303, Analytic N=222 (Attrition: 27%); Power: Assuming the true difference was 0.73 kg (1/3 of the equivalence margin) and common SD of 4.2 kg, a sample size of 63 per arm was required using two, one-sided t-tests to ensure at least 80% power with an alpha level of P< 0.05 to establish equivalence; Participant characteristics at baseline: Adults with overweight or obesity at baseline; - Age: ~48y; - Female: 82%; - Race and/or Ethnicity: ~62% White, ~28% Black/African American; - SEP: NR; - Anthropometry: Mean body weight: ~94kg; Mean BMI ~33.5 kg/m2; - Physical activity: No more than 300 minutes/wk (inclusion criterion); - Smoking: NR; - Diet quality: NR; - TEI: NR; Inclusion criteria: age 21–65y; BMI 27–40 kg/m2; weight stable within 10 lb during past 6 mo; no more than 300 min of physical activity weekly; drinking non-nutritive sweetener (NNS) beverages at least 3 times/wk; willing to discontinue NNS beverages if randomized to water group; physician approval stating that they were in good general health; Exclusion criteria: women who were lactating or pregnant during previous 6mo or planning on becoming pregnant; diabetes, CVD, uncontrolled hypertension, other diseases potentially interfering with weight loss, e.g., gastrointestinal or thyroid disease) or who used medications affecting weight and metabolism | Intervention: NNS group, n=158: asked to consume ≥24 fl oz/d (710 mL) of NNS beverages for 1y, with unrestricted water consumption. Premixed beverages containing NNS and <5 kcal/8-oz serving (237 mL) qualified as NNS beverages; Other interventions: All participants: 12wk weight loss phase: weekly, 60-min instructional classes from weight loss intervention; 40wk weight maintenance phase: 9 monthly group meetings, weighed monthly, advised to consume 25–35% of calories from fat and include 6d/wk of unsupervised exercise; Participants given coupons redeemable for monthly supply of NNS beverages or bottled water; Study beverage intake at baseline: Included: drink NNS beverages 3/wk; Comparator: Water group, n=150: asked to consume ≥24 fl oz/d (710 mL) of water for 1y and refrain from NNS beverage consumption. Instructed to not add NNS to beverages such as coffee/tea; permitted to consume foods with NNS, although not instructed to do so; Duration: 1y (first 12wk weight loss; next 40wk weight maintenance); Compliance: Participants were asked to record their daily beverage intake using paper logs; compliance was 98.1% (NNS) and 97.8% (water); Outcomes Assessment Methods and Timing:; Height measured with stadiometer; Weight measured on a digital scale. WC measured at top of iliac crest, based on 2 consecutive measures; Baseline, 12wk, 52 wk | [underlined: WC at 1y], cm, Mean (SD), per protocol, compound symmetry model; Over time, within group: Baseline, 52 wk, change; Water (n=107): 107.10 (0.91), 102.93 (1.00), −4.17 (0.83) cm, P<0.001; NNS (n=115): 108.00 (0.89), 99.33 (0.97), −8.67 (0.80) cm, P<0.001; Change between groups, NNS - water: −4.50 (1.16) cm, P<0.001; [underlined: Weight loss at 1y], kg, Mean (SD), ITT, Sattherwaite two‐sample t‐test; Over time, within group: Baseline, 52 wk, Change; Water: 93.15 (12.94); 90.70 (13.70), −2.45 (5.59) kg, P<0.001; NNS: 93.91 (13.46); 87.70 (14.79), −6.21 (7.65) kg, P<0.001; Change between groups, NNS - water: −3.76 (6.72), P<0.001; [underlined: % Achieved 5% weight loss], ITT, Chi-squared analysis; Water (n=149): 25.5%; NNS (n=154): 44.2%, P<0.001 | Model adjustments:; - TEI: no; - Other:; Limitations:; - Allocation and concealment NR; Funding:; American Beverage Association
Tate, 2012^43^; RCT-Parallel, Choose Healthy Options Consciously Everyday (CHOICE), U.S.; Baseline N=318, Analytic N=272 (Attrition: 15%); Power: With 100 participants per arm and a set at 0.05, study had 90% power to detect a difference of 1.8 kg with an SD of 3.4 kg and 25% attrition; Participant characteristics at baseline: Adults with overweight or obesity; - Age: Mean (SD): 42 (10.7)y (Range 18–65y); - Female: 84%; - Race and/or Ethnicity: 54% Black, 40% white, and 6% other; - SEP: college graduate or beyond ~55%; - Anthropometry: BMI ~36.3 (Range 25–49.9); - Physical activity: NR; - Smoking: 9% current smoker; - Diet quality: NR; - TEI: NR; Inclusion criteria: adults with overweight or obesity [BMI (kg/m2): 25–49.9] aged 18–65 y who reported consuming ≥280 kcal/d of caloric beverages; willing to make a dietary substitution for the study; Exclusion criteria: recent wt loss of >5%, participation in other wt-loss or physical-activity research; lactation; recent or planned pregnancy, thyroid medication use, diabetes treated with oral medication or insulin; cancer in the prior 5y; history of myocardial infarction or heart surgery; current psychiatric treatment; psychiatric hospitalization in past year; alcohol dependence assessed with the Rapid Alcohol Problems Screen; plans to move or unable to attend monthly group meetings; inadequate means to transport beverages; self-report of heart problems, frequent chest pains, or faintness or dizziness on the Physical Activity Readiness Questionnaire | Intervention: Diet beverages, n=105: replace ≥2 svg/d (≥200 kcal) caloric beverages with diet beverages which were provided at monthly group meetings; 4 355–500-mL (12–16 oz) single-svg beverages per person/d were provided; Comparator: “Attention Control” (AC, n=105): equal treatment contact time and attention, monthly group sessions and weigh-ins, weekly monitoring; given general weight-loss information but not given calorie-reduction or physical activity goals and not encouraged to change beverage intake; no beverage provision; 2nd Intervention Group: (Water, n=108): replace ≥2 svg/d (≥200 kcal) caloric beverages with water which was provided at monthly group meetings; four 355–500- mL (12–16 oz) single-svg beverages per person/d provided; Study beverage intake at baseline: ~100–200 g/d (see Figure 2); Duration: 6mo; Compliance: unannounced 24-h dietary recalls; group-specific study website where beverage intake was recorded. Intakes of the noncaloric beverage substitutions were in the expected direction based on intervention assignment.; Outcomes Assessment Methods and Timing:; Wt measured after 12h fast using digital scale; Height measured using stadiometer at baseline. WC measured at the iliac crest Baseline, 3mo, 6mo | [underlined: Waist circumference], cm, within group, over time: baseline, 3mo, 6mo, mean (95% CI); Control: 116.5 (113.9, 119.2), 116.8 (114.1, 119.5), 115.9 (113.2, 118.7), P=0.0107; Water: 115.1 (112.6, 117.6), 114.4 (111.9, 116.9), 113.1 (110.5, 115.8), P=0.0103; Diet beverages: 115.5 (112.5, 118.5), 114.9 (112.0, 117.8), 113.4 (110.5, 116.4), P=0.0103; Group x time interaction: control (ref); Diet bevs: P=0.21; Water: P=0.22; [underlined: Weight], kg, within group, over time: baseline, 3mo, 6mo, mean (95% CI); Control: 102.6 (99.1, 106.1), 101.1 (97.7, 104.6), 100.7 (97.2, 104.2), P<0.0001; Water: 98.4 (95.2, 101.6), 97.2 (94.0, 100.4), 96.5 (93.3, 99.7), P<0.0001; Diet beverages: 100.9 (97.1, 104.7), 99.0 (95.3, 102.7), 98.3 (94.5, 102.1), P<.0001; Group x time interaction: control (ref); Diet bevs: P=0.24; Water: P=0.99; [underlined: Likelihood of achieving 5% weight loss], OR (95% CI); Control: (ref); Diet beverages: 2.29 (1.05, 5.01), P=0.004 | Model adjustments:; - TEI: no; Limitations:; - Amount of carbonated and/or caffeinated versions of beverages was not taken into account; Trial registry did not include data analysis plan; Funding:; Nestle’ Waters USA
Vazquez-Duran, 2016^44^; RCT-Parallel, Mexico; Baseline N=148, Analytic N=146 (Attrition: 1%); Power: sample size of 31, which was increased by 20% loss to follow up, gave a total of 37 patients in each group. α=0.05, β=80% to detect −1.6% change in BMI in intervention group with SD 0.8; Participant characteristics at baseline: Adult nursing students; - Age: Mean (SD): 21.99 (0.25) y; - Female: 81%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: BMI, mean (SD): 26.24 (0.36) kg/m2; Overweight: 45%; Obesity: 16%; - Physical activity: <1hr/d of vigorous physical activity (inclusion criterion); - Smoking: NR; - Diet quality: NR; - TEI: NR; Inclusion criteria: nursing students from the School of Nursing of the Instituto Nacional de Ciencias Médicas y Nutrición Salvador Zubirán, male and female gender, more than 18 years of age and consumed at least 12 ounces of sweetened beverages/d (based on values from the Mexican Ministry of Health).; Exclusion criteria: on a special diet, arterial hypertension, diagnosed with or without use of antihypertensive medications, hyperthyroidism or hypothyroidism, use of weight loss medications, diabetes mellitus, cardiovascular or psychiatric diseases or hormonal therapy, participated in vigorous physical activity for more than one hour/d | Intervention: Only beverages with non-caloric sweeteners allowed (including plain water, lemon and hibiscus flavored water, coffee and tea without sugar), n=50; Comparator: No sweetened beverages permitted (only plain water, lemon and hibiscus flavored water, coffee and tea without sugar), n=49; Study beverage intake at baseline: NR; Duration: 6 mo; Compliance: 24hr food record 1x/week for full 6-month intervention; Outcomes Assessment Methods and Timing:; Weight and height measured according to anthropometric standardization reference manual; Body composition (resistance/height and phase angle) evaluated by bioelectric impedance analysis; Waist, hip, and arm circumferences evaluated according to the anthropometric reference manual Baseline, 3mo and 6mo follow-up | All Linear regression, Mean (SD), per protocol; [underlined: Waist Circumference % change]; Change over time, within group: 3mo, 6mo ASB: −1.56 (0.46), −1.23 (0.58); Without sweetened beverages: −2.45 (0.44), −4.07 (0.54); Change over time, between groups: 6mo, P<0.001; [underlined: Hip Circumference % of change]; Change over time, within group: 3mo, 6mo ASB: −0.71 (0.35), −0.35 (0.46); Without sweetened beverages: −1.63 (0.30), −3.00 (0.44); Change over time, between groups: 6mo P=NS; [underlined: Resistance/Height % of change]; Change over time, within group: 3mo, 6mo ASB: −0.85 (1.49), 2.00 (1.38); Without sweetened beverages: −1.92 (1.61), −2.12 (0.95); Change over time, between groups, 6mo: P=0.02; [underlined: Phase angle % of change]; Change over time, within group: 3mo, 6mo ASB: 5.57 (1.20), 4.92 (1.28); Without sweetened beverages: 4.88 (0.76), 8.40 (0.85); Change over time, between groups, 6mo:; P=NS; [underlined: BMI % of change]; Change over time, within group: 3mo, 6mo ASB: −0.61 (0.08), 0.11 (0.06); Without sweetened beverages: −1.75 (0.6), −3.34 (0.75); Change over time, between groups, 6mo: P<0.001 | Model adjustments:; - TEI: yes; Limitations:; †; Funding:; Instituto Nacional de Ciencias Medicas y Nutricion Salvador Zubiran
Bes-Rastrollo, 2006^18^; PCS, Seguimiento Universidad de Navarra (SUN), Spain; Analytic N=7,194; Participant characteristics at baseline: Adult university graduates; - Age: Mean ~36y; - Female: ~60%; - Race and/or Ethnicity: NR; - SEP: All university graduates; - Anthropometry: Mean~67kg; - Physical activity: Mean~19 MET-hr/wk; - Smoking: ~25% current smokers; 27% former smoker; - Diet quality: Range of means among quintiles; Fiber intake: 24–42 g/d; Intake of hamburgers, pizza, sausages: 17–30 g/d; Snacking between meals: 28–50%; - TEI: Mean~2575 kcal/d; Study beverage intake at baseline: NR; Inclusion criteria: SUN cohort participants who had already been followed-up for ≥2 y.; Excluded: extremely low or high values for total energy intake (<800 or >4200 kcal/d for men and<600 or >3500 kcal/d for women), missing values for the variables of interest, biologically implausible values for weight or height | Exposure: Diet soda; Other Exposures: SSB; Comparator: Continuous intake, mL/d; Exposure Assessment Methods and Timing:; Validated semi-quantitative FFQ; - Baseline; Outcomes Assessment Methods and Timing:; Weight was self-reported. Weight gain during follow-up defined categorically (any increase ≥ 1kg during follow-up) and continuously (difference between weight at baseline and follow-up); - Baseline, median 28.5mo follow-up | [underlined: Risk of weight gain], multivariate regression; P=NS, data NR | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, anthropometry at baseline, physical activity, diet quality (fiber intake, snacking between meals, fast food intake (hamburgers, pizza, sausages)), smoking; - Other: milk intake; alcohol intake; television watching; weight gain ≥3 kg in the past 5y; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Exposure data only measured at baseline; No information on non-completers; Weight was self-reported; No preregistered data analysis plan; Funding:; Department of Health of the Navarre Regional Government; Spanish Ministry of Health
Bes-Rastrollo, 2008^19^; PCS, Nurses' Health Study II, U.S.; Analytic N=50,026; Participant characteristics at baseline: Adult women; - Age: Mean (SD): 36.5y (4.6); - Female: 100%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: Mean (SD): BMI: 24.2 (5.0); Weight, kg: 65.9 (14.3); - Physical activity: MET-h/wk, Mean (SD): 20.4 (26.4); - Smoking: Current: 11%; - Diet quality: Dietary energy density, kcal/g (food only): 1.2 (0.4); Dietary energy density, kcal/g: 1.1 (0.3); Food group intake, Mean (SD):; Vegetables, g/d: 159 (99); Fruit, g/d: 176 (118) Other macronutrient and food group intakes reported in paper; - TEI: Mean (SD), 1771 (522) kcal/d; Exclusion criteria: missing dietary (completely missing or >9 missing items), physical activity, weight, or follow-up data; unreasonable energy intakes; history of diabetes or CVD; cancer; pregnancy | Exposure: Low calorie cola, Low calorie caffeine free cola; Other Exposures: SSB, 100% juice, milk, coffee, tea; Comparator: Categorical intake (tertiles); Exposure Assessment Methods and Timing:; Self-administered semi-quantitative FFQ; Represents intake during previous year; Baseline, 8y; Outcomes Assessment Methods and Timing:; Weight, self-reported through biennial questionnaires; - Baseline, 8y | [underlined: Weight change over 8y], kg, Linear regression; Low-calorie cola over 8y; Lowest tertile (ref) vs Highest tertile: Data NR, P=NS; Low-calorie, caffeine-free cola over 8y Lowest tertile (ref) vs Highest tertile: Data NR, P<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex, age, physical activity, smoking; - Other: Postmenopausal hormone use, oral contraceptive use, changes in confounders between time periods; Limitations:; - Did not account for key confounders: Race and/or Ethnicity, SEP, anthropometry at baseline, diet quality; - Exposures not well defined and FFQ varied over time; No info on non-completers; Self-reported weight; No preregistered data analysis plan; Funding:; NIH; Spanish Ministry of Education; Fundacion Caja Madrid; Amigos de la Universidad de Navarra; AHA Established Investigator Award
Buso, 2022^21^; PCS, Lifelines Cohort Study, Netherlands; Analytic N=78,286; Participant characteristics at baseline: Adults; - Age: Mean (SD): 46y (13); - Female: 60%; - Race and/or Ethnicity: NR; - SEP: Education: Low (<secondary school): 4%; Intermediate (secondary school but <Bachelor's): 65%; High (Bachelor's, Master, or PhD): 31%; - Anthropometry: Mean (SD): Weight (kg): 79.5 (15), BMI (kg/m2): 26 (4.2), WC (cm): 90.1 (12.2) BMI <25: 45%; - Physical activity: METs min/wk: Median [25th, 75th percentile]: Intense: 0 [0, 630], Moderate: 1,665 [806, 2,948], Sedentary (minutes/wk): 840 [630, 1,260]; - Smoking: Never 47%; Former 35%, Current 18%; - Diet quality: Median (25th-75th%) serv/d SSB: 0.11 (0.0, 0.61); - TEI: Median [25th, 75th percentile]: 1,977 [1,640, 2,380] kcal/day; Inclusion criteria: available data on body weight and waist circumference change; Exclusion criteria: severe psychiatric or physical illness, limited life expectancy (<5 years), insufficient knowledge of Dutch language, unreliable dietary data (TEI <500 or >3,500 kcal/day for women and <800 and >4000 for men), missing data on body weight change, waist circumference change, or covariates | Exposure: Diet soda or light soda, 150 mL = standard serving; Other Exposures: SSB; Comparator: Continuous intake (svg/d); Exposure Assessment Methods and Timing: semi-quantitative 110-item FFQ Baseline (2006–2013); Study beverage intake at baseline: Median [25th, 75th percentile] 0.01 [0.0, 0.61] svg/day; 57% consumed LNCSB; Outcomes Assessment Methods and Timing:; Height, weight, and waist circumference measured by trained professionals; change in weight and WC calculated by weight follow-up – weight baseline)/years of follow-up and WC follow-up – WC baseline)/years of follow-up; overweight/obesity defined by BMI ≥25 kg/m2 at follow-up and abdominal obesity as WC >94 cm for men and >80 cm for women; - Baseline (2006–2013) and 1–9y later (Median: 4y) | [underlined: Waist circumference change], cm/y, by baseline LNCSB intake (serving/d), β (SE), Linear regression:; TEI not adjusted: 0.11 (0.01); TEI adjusted: 0.11 (0.01); Stratified by BMI (<25, ≥25): p=0.06; Sex: p=0.87, Age (<46y, ≥46): p=0.71; Dose-reponse associations, β (SE), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: 0.08 (0.02); 1-2serv/d: 0.20 (0.03); >2 serv/d: 0.40 (0.04); P non-linear = 0.07; Stratified by BMI (<25, ≥25): p=0.09; Sex: p=0.76; Age (<46y, ≥46): p=0.25; [underlined: Abdominal obesity incidence by baseline LNCSB intake], IPR (95% CI), Cox proportional hazards regression (6,896 cases in 31,292 without abdominal obesity at baseline):; TEI not adjusted: 1.05 (1.02, 1.07); TEI adjusted: 1.05 (1.02, 1.07); Stratified analyses (TEI adjusted): Sex: p=0.04, Age (<46y, ≥46): p=0.75; Dose-reponse associations, IPR (95% CI), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: 0.99 (0.95, 1.04); 1–2serv/d: 1.01 (0.93, 1.08); >2 serv/d: 1.06 (0.95, 1.16); P non-linear = 0.15; Stratified analyses (TEI adjusted): Sex: p=0.22; Age (<46y, ≥46): p=0.78; [underlined: Weight change], kg/y, by baseline LNCSB intake (serving/d), β (SE), Linear regression:; TEI not adjusted: 0.06 (0.01); TEI adjusted: 0.06 (0.01); Stratified by BMI (<25, ≥25): p=0.001;; Sex: p=0.27, Age (<46y, ≥46): p=0.05; Dose-response associations, β (SE), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: 0.03 (0.01); 1-2serv/d: 0.09 (0.02); >2 serv/d: 0.20 (0.03); P non-linear = 0.75; Stratified by BMI (<25, ≥25): p<0.001;; Sex: p=0.54; Age (<46y, ≥46): p=0.16; [underlined: Overweight/Obesity incidence by baseline LNCSB intake] (serving/d), IPR (95% CI), Cox proportional hazards regression (4,884 cases in 35,202 normal BMI at baseline):; TEI not adjusted: 1.08 (1.05, 1.11); TEI adjusted: 1.08 (1.06, 1.11); Stratified analyses (TEI adjusted): Sex: p=0.30, Age (<46y, ≥46): p=0.34; Dose-response associations, IPR (95% CI), restricted cubic spline analysis, TEI adjusted:; 0 serv/d: REF; ≤1 serv/d: 0.94 (0.88, 1.00); 1–2serv/d: 0.92 (0.83, 1.01); >2 serv/d: 1.16 (1.04, 1.28); P non-linear = 0.04; Stratified analyses (TEI adjusted): Sex: p=0.62; Age (<46y, ≥46): p=0.26 | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, socioeconomic position (education), anthropometry at baseline (height, weight, BMI or WC), physical activity, diet quality (meat, dairy, legumes, vegetables, nuts, fruits, potatoes, fats, grains, tea, coffee, sugary food intakes and other beverages (SSB)), smoking; - Other: alcohol intake, history of disease (self-reported diabetes and history of CVD, hypertension, and hypercholesterolemia), sedentary behavior; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; EU-project under the acronym SWEET has received funding from the European Union’s Horizon 2020 research and innovation programme, grant agreement No. 774293
Chen, 2009^22^; PCS, Secondary analysis of PREMIER randomized trial, U.S.; Analytic N=810; Participant characteristics at baseline: adults enrolled in an 18mo behavioral intervention trial to lower blood pressure; - Age: Mean (SD) = 50 (8.9) y, Range 25–79y; - Female: 62%; - Race and/or Ethnicity: African American: 34.4%, Non-Hispanic White: 64.2%, All Others: 1.4%; - SEP: 57.2% college degree or above; 70% annual household income >$45,000, 65.2% married; - Anthropometry: BMI Mean (SD): 33.1 (5.8) kg/m2; 65.2% BMI ≥ 30, 29% BMI 25.0–29.9, 5.4% BMI < 25; - Physical activity: EER Mean (SD) 33.7 (2.9) kcal/kg•d; - Smoking: 4.8% current smokers; - Diet quality: Liquid calorie intake, Mean (SD): 356 (237) kcal/d % of total energy intake from liquid calories, Mean (SD): 19 (11.5); - TEI: NR; Inclusion criteria: Trial included adults with prehypertension or stage 1 hypertension (systolic BP 120–159 mmHg and diastolic BP 80–95 mmHg).; Exclusion criteria: individuals who routinely used antihypertensive medications, weight loss medication, or oral steroids. Also excluded those with diabetes, history of a cardiovascular event, CHF, current symptoms of angina or PVD, cancer diagnosis or treatment in past 2y (except for nonmelanoma skin cancer), renal insufficiency, or psychiatric hospitalization within the past 2y | Exposure: Diet drinks (diet soda and other "diet" drinks sweetened with artificial sweeteners); 1 svg = 12 fl oz or 355 mL; Other Exposures: SSB, milk, 100% juice, coffee and tea with sugar, coffee and tea without sugar; Comparator: Continuous intake (12-oz svg/d); Exposure Assessment Methods and Timing:; Two 24h dietary recalls (1 weekday and 1 weekend day) via telephone interviews using multiple-pass and portion size estimation aids; - At baseline, 6mo, and 18mo; Study beverage intake at baseline: Mean (SD) = 331.2 (414.0) mL/d; Outcomes Assessment Methods and Timing:; Weight measured using calibrated scale; - At baseline, 6mo, and 18mo | [underlined: Change in weight (kg) according to reduction in diet drink intake by 1 svg/d], β (95% CI); At 6mo: −0.27 (−0.60, 0.05), p=0.11; At 18mo: −0.38 (−0.22, 0.01), p=0.06 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Other: intervention group; Limitations:; - No preregistered data analysis plan; Funding:; NHLBI; NIH; Center for Human Nutrition, Johns Hopkins Bloomberg School of Public Health; NICHD
Duffey, 2012^23^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA), U.S.; Analytic N=3,524; Participant characteristics at baseline: Young adults; - Age: ~25y; - Female: 63%; - Race and/or Ethnicity: Black ~62%; - SEP: Education:; High School: ~35%, Some College: ~39%, College: ~32%; - Anthropometry: BMI ~24.5 kg/m2; Overweight: ~23%, Obesity: ~10%; - Physical activity: ~425 EU/wk; - Smoking: Former: ~15%; Current: ~36%; Never: ~67%; - Diet quality: Prudent dietary pattern: 42.7%; - TEI: NR; Exclusion criteria: missing outcome or covariate data, high WC at baseline | Exposure: Diet beverage intake; Other Exposures: None; Comparator: Categorical: consumers vs. non-consumers; Exposure Assessment Methods and Timing:; - Validated CARDIA Diet History questionnaire (interviewer-administered), asks about general dietary practices; - Quantitative diet history, represents consumption over the previous month; - Baseline; Study beverage intake at baseline: Diet beverage consumers at baseline: 22%; Outcomes Assessment Methods and Timing:; Waist circumference (WC) measured at the minimum abdominal girth by trained technicians; average of 2 measures used for analysis. High WC: >35 in (>88 cm) for women or >40 in (>102 cm) for men; - At baseline, and 2, 5, 7, 10, 15, and 20y follow-up | [underlined: High WC], Proportional hazards, HR (95% CI); Consumer (ref) vs.; Non-consumer: 0.84 (0.73, 0.97), P<0.05; Western Consumers (ref) vs.; Western Non-consumers: 0.85 (0.70, 1.04); Prudent Consumers: 0.93 (0.73, 1.17); Prudent Non-consumers: 0.78 (0.62, 0.97); P-interaction: 0.943 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, Race and/or Ethnicity, SEP, anthropometry at baseline, physical activity, smoking, diet quality (Prudent or Western dietary pattern); - Other: CARDIA study center; Limitations:; - Attrition 31% without information on non-completers; Exposure measured only at baseline; No preregistered data analysis plan; Funding:; NIH; UNC-CH Center for Environmental Health and Susceptibility; UNC-CH Clinic Nutrition Research Center; Carolina Population Center; University of Alabama at Birmingham, Field Center; University of Minnesota, Field Center; Northwestern University, Field Center; Kaiser Foundation Research Institute (NHLBI)
Ferreira-Pego, 2016^24^; PCS of RCT data, PREDIMED (PREvención con Dieta MEDiterránea), Spain; Analytic N=1,868; Participant characteristics at baseline: adults at high risk for CVD; - Age: Mean (SD): 67y (6); - Female: 53%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean (SD): 28.3 (3.5) kg/m2; - Physical activity: Leisure time MET, minutes/d, Mean (SD): 274 (252); - Smoking: Never: ~58%; Current; ~17%; Former: ~26%; - Diet quality: Mean (SD), g/d Vegetables: ~334 (152); Fruit: ~359 (199); - TEI: Mean (SD): 2,323 (~530) kcal/d; Inclusion criteria: no CVD at baseline but increased risk indicated by type 2 diabetes or ≥3 of (smoking, hypertension, high LDL cholesterol, low HDL cholesterol, overweight/obesity, family history of premature CVD); Exclusion criteria: Severe chronic illness, drug/alcohol addiction, history of allergy/intolerance to olive oil or nuts, low predicted likelihood of changing dietary habits, MetS (or missing diagnostic data), missing FFQ, implausible TEI | Exposure: Artificially sweetened beverages (LNCSBs); 1 svg=200mL; Other exposures: SSB, 100% juice; Comparator: Categorical intake: <1 svg/wk, 1–5, >5; Exposure Assessment Methods and Timing: Validated FFQ assessing habitual intake for previous year; - Baseline, annually for ≥2y (intake was averaged across all time points for analyses); Study beverage intake at baseline:; During follow up: Mean 17.1 mL/d; Outcomes Assessment Methods and Timing:; Weight: measured by trained personnel with calibrated scales. Height: measured by trained personnel with a wall-mounted stadiometer. Waist circumference measured using an anthropometric tape midway between the lower rib and the superior border of the iliac crest. Abdominal obesity: waist circumference ≥88cm in women and ≥102 cm in men; - Baseline, annually for ≥2y | [underlined: Abdominal obesity], Multivariable time-dependent Cox proportional regression, HR (95% CI); LNCSB average intake across time:; <1 svg/wk: Ref; 1–5 svg/wk: 0.91 (0.65, 1.28); >5 svg/wk: 1.82 (1.13, 2.92); P for trend: 0.039 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (vegetables, legumes, fruit, cereals, meat, fish, bakery, dairy products, olive oil, and nuts); - Other: alcohol (overall alcohol intake & alcohol squared in grams per day), intervention group, prevalence of metabolic syndrome components at baseline; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - No information on whether or not amount of missing data varied across exposure groups; Follow-up time differs among participants; No preregistered data analysis plan; Funding:; Spanish Ministry of Health, the Thematic Network, FEDER (European Regional Development Fund), the Centre Catalá de la Nutrició de l’Institut d’Estudis Catalans, and the Fundació ‘‘LaMarat´ o de TV3’’
Fowler, 2015^25^; PCS, San Antonio Longitudinal Study of Aging (SALSA), U.S.; Analytic N=466; Participant characteristics at baseline: Older adults; - Age: 69y (all ≥65y); - Female: 60%; - Race and/or Ethnicity: ~50% Mexican-American; ~50% European-American; - SEP: ~35% suburb residents; ~20% barrio residents; - Anthropometry: BMI: ~29 kg/m2; WC: ~100cm; Overweight/Obesity: ~78%; - Physical activity: Leisure time energy expenditure ~1800 kcal/wk; - Smoking: Current: 10%; - Diet quality: SSB, frequency/day; LNCSB consumers: 0.02; LNCSB non-consumers: 0.30; - TEI: NR; Inclusion criteria: participant in existing CVD risk cohort among Mexican Americans and European Americans; Exclusion criteria: missing covariate data | Exposure: Diet soda intake (sugar-free soda); Other Exposures: SSB; Comparator: Categorical intake:; - None/Non-users: 0–0.05 diet sodas/d; - Occasional users: >0 but <1 soda/d; - Daily users: ≥1 soda/d; Exposure Assessment Methods and Timing:; Questionnaire; represents weekly intake; non-validated; - At baseline and beginning of each follow-up interval (~7y, 8.5, 10y from baseline); Study beverage intake at baseline: None/Non-users: 0–0.05 diet sodas/d, n=255; Occasional users: >0 but <1 soda/d, n=89; Daily users: ≥1 soda/d, n=40; Outcomes Assessment Methods and Timing:; - Height and weight measured; - BMI calculated as kg/m2; - Waist Circumference (WC) measured in cm at the level of the umbilicus; At baseline, 3 follow-ups: FU1 ~7y, FU2 ~1.5y; FU3 ~1.5y; total ~9.4y (range 4.5–12.5y) | [underlined: Change in WC], cm, over interval, By diet soda consumption category, Mean (95% CI); None/Non-User: 0.77 (0.29, 1.23) (ref); Occasional (>0 and <1): 1.76 (0.96, 2.57); Daily (≥1): 3.04 (1.82, 4.26), P<0.001; P-trend= 0.002; Subgroup Analyses: N=person-years; [underlined: Overall:] P-diff<0.001; None (N=2405): 0.77 (0.29, 1.23); Any (n=1301): 2.11 (1.45, 2.76); [underlined: Men:] P-diff=0.002; P-interaction=0.154; None (n=955): 0.29 (−0.47, 1.05); Any (n=526): 2.31 (1.30, 3.32); [underlined: Women:] P-diff=0.139; None (n=1450): 1.09 (0.47, 1.71); Any (n=774): 1.92 (1.05, 2.79); [underlined: Mex-Amer:] P-diff=0.150; P-interaction=0.439; None (n=1299): 0.76 (0.07, 1.46); Any (n=517): 1.71 (0.67, 2.75); [underlined: European-American:] P-diff=0.005; None (N=1106): 0.80 (0.10, 1.49); Any (N=784): 2.40 (1.55, 3.25); [underlined: BMI<25:] P-diff=0.833; None (N=623): 1.70 (0.68, 2.72); Any (N=205): 1.92 (0.10, 3.74); [underlined: BMI 25–30:] P-diff=0.067; P-interaction<0.001; None (N=1076): 1.19 (0.55, 1.84); Any (N=575): 2.24 (1.38, 3.10); [underlined: BMI≥30:] P-diff=0.031; P-interaction<0.001; None (N=701): −0.53 (−1.68, 0.62); Any (N=512): 1.53 (0.19, 2.87); [underlined: Change in BMI], kg/m2, over interval, By diet soda consumption category, Mean (95% CI); None: −0.41 (−0.57, −0.25) (ref); >0 and <1: −0.11 (−0.38, 0.16); ≥1: 0.05 (−0.35, 0.45), P<0.043; P-trend= 0.049 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, Race and/or Ethnicity, SEP, anthropometry at baseline, physical activity, smoking; - Other: Diabetes, length of follow-up interval; Limitations:; - Did not account for key confounders: Diet quality; - Exposure data collection tool not validated; No preregistered data analysis plan; Funding:; NIA; NIDDK; NCRR; CTSA
Fowler, 2008^26^; PCS, San Antonio Heart Study, U.S.; Analytic N=3,371; Participant characteristics at baseline: Adults; - Age: Mean~44y (Range=25–64y); - Female: 58%; - Race and/or Ethnicity: Non-Hispanic White: 36%; Mexican American: 64%; - SEP: Education: Mean~12y Socioeconomic index: Mean~51; - Anthropometry: Mean BMI: ~27 kg/m2 With Overweight ~65%, With Obesity ~25%; - Physical activity: Currently exercising ~27%; Exercise frequency, Mean~1.7 times/wk; - Smoking: 26% current smokers; - Diet quality: NR; - TEI: Mean~1900 kcal/d; Study beverage intake at baseline: ASB intake: Mean~1 drink/d;; Diet soda intake: Mean~0.4 drink/d; Inclusion criteria: cohort of Mexican Americans and non-Hispanic whites; age 25–64y at baseline; residing in San Antonio, TX; follow-up exam data 7–8y after baseline; baseline ASB dose, baseline and follow-up BMI, and all covariate data available | Exposure: ASB (including diet soft drinks and artificially sweetened tea and coffee); Diet soft drinks (sugar-free sodas); Other Exposures: SSB, coffee, tea; Comparator: Categorical (quartiles, drinks/wk): None (ref), Q1: <3, Q2: 3–10, Q3: 11–21, Q4: ≥22; For diet soft drinks: no use vs any use; Exposure Assessment Methods and Timing:; ASB consumption estimated by summing intakes of artificially sweetened soda, coffee, and tea (from beverages and sweeteners added to beverages). Dose was set to zero for abstainers.; - Baseline; Outcomes Assessment Methods and Timing:; Weight categories defined as follows: normal wt, BMI<25 kg/m2; with overweight, BMI ≥25 and <30 kg/m2; with obesity, BMI ≥ 30 kg/m2. Incidence of overweight or obesity defined as % of participants with normal weight who had overweight or obesity by follow-up. Change in BMI calculated as BMI at follow-up minus baseline BMI; - Baseline, 7–8y follow-up | By artificially-sweetened beverage intake; [underlined: Incidence of overweight and obesity], OR (95% CI); Q1 (ref) vs; Q2: 1.56 (1.02, 2.40), P=0.041; Q3: 1.74 (1.10, 2.77), P=0.018; Q4: 1.75 (1.09, 2.82), P=0.021; Q5: 1.93 (1.20, 3.11), P=0.007; Overall P=0.008 P for trend<0.001; [underlined: Incidence of obesity], OR (95% CI); Q1 (ref) vs; Q2: 1.34 (0.86, 2.08), P=NS; Q3: 1.46 (0.96, 2.22), P=0.075; Q4: 1.73 (1.13, 2.63), P=0.011; Q5: 2.03 (1.36, 3.03), P=0.0005; Overall P=0.005; P for trend<0.0001; [underlined: Change in BMI] (kg/m2), Mean (SE); Q1: 1.01 (0.88, 1.14), P=NS; Q2: 1.11 (0.85, 1.38), P=NS; Q3: 1.46 (1.20, 1.73), P=0.003; Q4: 1.50 (1.23, 1.78), P=0.002; Q5: 1.78 (1.51, 2.06), P<0.0001; P for trend<0.0001; Similar results obtained for change in BMI in sub-analyses excluding interim artificial sweetener adopters and discontinuers; By diet soft drink intake; [underlined: Change in BMI] (kg/m2), Mean (SE) No use (n=2301): 1.10 (0.06); Any use (n=1070): 1.52 (0.09); Mean difference = 0.42 (0.21, 0.63), P<0.0001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity (baseline and interim change), smoking (baseline and interim change); - Other:; Limitations:; - Did not account for key confounders: diet quality; - Exposure assessment tool not validated; Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; NIH; USDA
Garduno-Alanis, 2020^27^; PCS, Health, Alcohol, and Psychosocial factors in Eastern Europe (HAPIEE); Russian cohort, Russia; Analytic N=5,205; Participant characteristics at baseline: Adults; - Age: <55y: 36%;; 55–65y: 40%;; >65y: 23%; - Female: 55%; - Race and/or Ethnicity: NR; - SEP: Education: primary or less 11%;; Vocational 27%; Secondary 34%; University degree 29%; Marital status: living with a partner −72% living without a partner - 28%; - Anthropometry: Mean (SD) BMI 28.5 (5.5) kg/m2; - Physical activity: MET-h/day: %of sample; <5 – 29%; 5–15 - 57%; >15–15%; - Smoking: Never: 58%; Ex-smoker 14%; Regular smoker 28%; - Diet quality: Fruit and vegetable consumption g/day: <300 – 38%; 300–600 - 45%; >600 – 17%; - TEI: Kcal/day: <2000 – 55.8%; 2000–2500 - 24.3%; >2500 – 19.9%; Exclusion criteria: missing data (exposure, outcome, and covariates), extreme values for weight (>200kg), height (>205 cm) and energy intake (>5000 kcal or <500kcal/day) | Exposure: Low calorie (diet) carbonated drinks; Other Exposures: SSB, 100% fruit juice; Comparator: Drinkers vs non-drinkers; Exposure assessment methods and timing: FFQ-country specific items and portion sizes, foods, and drinks. Frequency in the last three months and answers converted to daily consumption.; - Baseline (2002–2005); Study beverage intake at baseline:; LNCSB consumption:; Never drink 97.2%; <1/day 2.2%; >1/day 0.6%; Outcomes Assessment Methods and Timing:; Height and weight measured in clinic by professional; missing data was replaced by self-reported measures (n=3085 at baseline); BMI calculated by body weight (kg)/square of height (m); obesity defined as BMI>30 kg/m2 ; change in BMI was calculated by subtracting BMI at baseline from BMI at follow up; Baseline (2002–2005) and follow up (2006-2008) | [underlined: Unit change in BMI]: OR (95% CI), multivariable logistic regression Nondrinkers = REF; LNCSB drinkers 1.63 (1.12–2.39), p=0.012 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, diet quality (F&V intake), smoking; - Other: Alcohol consumption, hx of disease (CVD, Diabetes, Cancer); Limitations:; - Did not account for key confounders: race and/or ethnicity; - Exposure not well defined; Exposure data only measured at baseline; Very low intake of target beverage (LNCSB); No information on non-completers; weight and height was/were self-reported (for missing baseline values); No preregistered data analysis plan; Funding:; Wellcome Trust, the US National Institute of Aging, and the MacArthur Foundation Initiative on Social Upheaval and Health
Gearon, 2018^28^; PCS, Melbourne Collaborative Cohort Study (MCCS), Australia; Analytic N=7,894; Participant characteristics at baseline: Adults; - Age: ~46y (Range 27–80y, focused on 40–69y); - Female: 61%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI: Women ~25 kg/m2, Men ~26 kg/m2; - Physical activity: leisure time score ~4; - Smoking: Never smoker: Women ~62%, Men ~52%; - Diet quality: Nutrient-rich foods consumption (times/wk), median (IQR): Women: Lower education: 8.5 (4.0, 18.0), Higher ed: 12.5 (7.5, 21.0); Men: Lower ed: 7.0 (2.0, 13.5), Higher ed: 9.5 (4.5, 18.5); Fruits and vegetables (times/d), median (IQR): Women: Lower ed: 7.4 (5.1, 10.0), Higher ed: 8.3 (6.0, 11.1); Men: Lower ed: 5.4 (3.4, 7.6), Higher ed: 6.5 (4.5, 8.9); SSB intake (% ≥weekly), n (%): Women: Lower education: 542 (29%), Higher education: 622 (21%); Men: Lower education: 382 (53%), Higher education: 1000 (42%); - TEI: NR; Inclusion criteria: 27–80y between 1990–1994 (recruitment efforts focused on healthy volunteers 40–69y); An arm of recruitment focused on migrants from Southern Europe; individuals born in Italy and Greece comprised 24% of the baseline population.; Exclusion criteria: missing data; southern European country of birth; >65y at follow-up; cancer or cardiometabolic conditions at baseline; BMI loss ≥5% from baseline; extreme energy intakes (1st or 99th percentile) | Exposure: Diet soft drinks; Other Exposures:; Comparator: Categorical: <1/mo vs. ≥ 1/mo; Exposure Assessment Methods and Timing:; FFQ designed for the study; based on frequency, not amount; not validated; - Baseline; Study beverage intake at baseline: 73% consumed diet soda never or <1 once per month; Outcomes Assessment Methods and Timing:; Weight, WC and height measured by practitioner; - Baseline, 13y follow-up (height only measured at baseline) | [underlined: BMI change over 13y], Diet soft drink; <1/mo vs ≥ 1/mo, Linear regression, β (95% CI); Women: 0.52 (0.38, 0.67), P<0.05; Men: 0.28 (0.15, 0.43), P<0.05 | Model adjustments:; - TEI: no; - Key confounders: sex, age, smoking; - Other: Alcohol intake; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality; - Bias due to missing data can’t be determined; Exposure data only measured at baseline; Exposure classified by frequency not amount; Exposure data collection tool not validated; No preregistered data analysis plan; Funding:; NHLBI; NCI
Hinkle, 2019^29^; PCS, Diabetes & Women’s Health Study (DWH), a sub-cohort of the Danish National Birth Cohort (DNBC), Denmark; Analytic N=607; Participant characteristics at baseline: Women with history of gestational DM during index pregnancy of Danish National Birth Cohort (DNBC); - Age: ~31y; - Female: 100%; - Race and/or Ethnicity: NR; - SEP: ≥High school education: 33%; - Anthropometry: Pre-pregnancy BMI ~27 kg/m2; - Physical activity: MVPA ~0 MET-h/wk; - Smoking: 26% smokers; - Diet quality: AHEI score: ~48.5; - TEI: ~2400 kcal/d; Inclusion criteria: Danish women enrolled in DNBC who were diagnosed with GDM during pregnancy and opted into DWH cohort; Exclusion criteria: implausible daily energy intake (<956 or >4780 kcal/d in baseline DNBC questionnaire and <600 or >4000 kcal/d in DWH follow-up questionnaire) | Exposure: Artificially sweetened beverages (ASBs included carbonated and noncarbonated sources, such as diet soda pop/Coca Cola without sugar, diet/light lemonade without sugar); 1 svg = 250 g; Other Exposures:; Comparator: ASB intake (categorical): <1 svg/mo (ref), 1–4 svg/mo, 2–6 svg/wk, ≥1 svg/d; Exposure Assessment Methods and Timing:; Validated semi-quantitative FFQ; represents habitual dietary intake during previous month (DNBC) or year (DWH); missing dietary data (27.8%) was imputed; - Baseline (25wk gestation during DNBC 1996–2002), and at 9–16y follow-up (during DWH, 2012–2014); Study beverage intake at baseline: ≥2 svg/wk: ASB intake during pregnancy: 30%; ASB intake at follow-up: 36%; Outcomes Assessment Methods and Timing:; Baseline: self-reported pre-pregnancy height and weight; Follow-up: Height and weight measured twice according to standardized protocol; BMI calculated as kg/m2. Waist circumference (WC) measured twice midway between lowest rib and iliac crest. Abdominal visceral adipose tissue measured in subset of women (n=192) using whole-body DXA and estimated using enCORE software. Obesity: BMI>30 kg/m2; - Baseline, 9–16y follow-up | [underlined: WC], Linear regression, % difference (95% CI); ASB in pregnancy (n=606);; <1 svg/mo: ref; 1–4 svg/mo: 2.0 (−0.5, 4.5); 2–6 svg/wk: 2.6 (0.3, 4.9); ≥1 svg/d: 1.6 (−1.1, 4.5); P-trend: 0.40; Habitual ASB (in pregnancy and follow-up) (n=606); ≤4 svg/mo (pregnancy and follow-up): ref; ≤4/mo (pregnancy) and ≥2/mo (follow-up): −0.8 (−3.2, 1.6); ≥2/wk (pregnancy) and ≤4/mo (follow-up): 1.7 (−1.4, 4.9); ≥2 svg/wk (pregnancy and follow-up): 1.0 (− 1.2, 3.3); P-trend=0.79; [underlined: Visceral Adipose Tissue], Linear regression, % difference (95% CI); ASB in pregnancy (n=192); <1 svg/mo: ref; 1–4 svg/mo: 27.6 (−14.4, 90.3); 2–6 svg/wk: 15.9 (−16.7, 61.4); ≥1 svg/d: 18.7 (−20.7, 77.7); P-trend: 0.54; Habitual ASB (in pregnancy and follow-up) (n=192); ≤4 svg/mo (pregnancy and follow-up): ref; ≤4/mo (pregnancy) and ≥2/mo (follow-up): −0.2 (−30.8, 43.7); ≥2/wk (pregnancy) & ≤4/mo (follow-up): 13.6 (−25.0, 72.1); ≥2 svg/wk (pregnancy and follow-up): 3.7 (− 26.4, 46.2); P-trend=0.55; [underlined: BMI], Linear regression, % difference (95% CI); ASB in pregnancy (n=606);; <1 svg/mo: ref; 1–4 svg/mo: 1.5 (−1.9, 5.1); 2–6 svg/wk: 2.7 (−0.4, 5.9); ≥1 svg/d: 1.0 (−2.9, 5.0); P-trend: 0.79; Habitual ASB (in pregnancy and f/u (n=606); ≤4 svg/mo (pregnancy and follow-up): ref; ≤4/mo (pregnancy) and ≥2/mo at follow-up: 1.5 (−2.7, 5.9); ≥2/wk (pregnancy) and ≤4/mo at follow-up: 3.5 (−0.2, 7.3); ≥2 svg/wk (pregnancy and follow-up): 1.5 (−1.7, 4.8); P-trend=0.52; [underlined: Obesity], Poisson regression, RR (95% CI); ASB in pregnancy (n=606);; <1 svg/mo: ref; 1–4 svg/mo: 1.20 (0.87, 1.64); 2–6 svg/wk: 1.43 (1.13, 1.82); ≥1 svg/d: 1.18 (0.89, 1.57); P-trend: 0.50; Habitual ASB (in pregnancy and f/u (n=606); ≤4 svg/mo (pregnancy and follow-up): ref; ≤4/mo (pregnancy) and ≥2/mo (follow-up): 1.18 (0.88, 1.59); ≥2/wk (pregnancy) and ≤4/mo (follow-up): 1.41 (0.98, 2.02); ≥2 svg/wk (pregnancy and follow-up): (1.04, 1.81); P-trend=0.26 | Model adjustments:; - TEI: no; - Key confounders: sex, age, SEP, anthropometry at baseline, physical activity, smoking, diet quality (Alternative Healthy Eating Index−2010); - Other: Parity, intake of tea and coffee, pre-pregnancy chronic diseases at the index pregnancy; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Follow-up and start of exposure differ among participants; No preregistered data analysis plan; Funding:; NICHD; March of Dimes Birth Defects Foundation; Innovation Fund Denmark; Health Foundation; Heart Foundation; European Union; Danish Diabetes Academy supports by Novo Nordisk Foundation
Konieczna, 2019^30^; PCS, Secondary analysis of PREDIMED trial, Spain; Analytic N=7,009; Participant characteristics at baseline:; Spanish older adults; - Age: Mean (SD): 67y (6.2); - Female: 58%; - Race and/or Ethnicity: All "white, elderly Spanish"; - SEP: Higher education/technician: 7%; - Anthropometry: Body weight, kg, mean (SD): 76.7 (12.0); WC, cm, mean (SD): 100 (10); BMI, kg/m2, mean (SD): 30.0 (3.8); Obesity prevalence: 47%; Abdominal obesity prevalence: 73%; - Physical activity: METs (min/d), mean (SD): 233 (239); - Smoking: Current smoker: 14%; - Diet quality: Adherence to MedDiet (14-points score), mean (SD): 9 (2); - TEI: Kcal/day, mean (SD): 2239 (543); Average yearly change (svg/d) during follow-up, mean (5th, 95th percentile): −0.01 (−0.20, 0.14); Inclusion criteria: age 55–80y, free of CVD at enrollment but at risk of CVD based on T2D diagnosis or ≥3 risk factors (hypercholesterolemia, low HDL, with overweight/obesity, hypertension, current smoking or family history of premature coronary heart disease); Exclusion criteria: missing data on waist circumference, physical activity, or FFQ at baseline (n=291), total energy intake values outside predefined limits (500–3500 kcal/d (women), 800–4000 kcal/d (men)) (n=147) | Exposure: Artificially-sweetened beverages (low-calorie soft beverages, light beverages). Exposure of interest was change in intake expressed in serving/d, calculated as the difference between yearly measured values and values from the previous year.; Other Exposures: Milk, SSB, 100% juice, coffee and tea; Comparator: Different intake of LNCSB (continuous, svg/d); Exposure Assessment Methods and Timing:; 137-item semi-quantitative FFQ; intake calculated by multiplying serving size by frequency of consumption (from never to > 6 times/d; - At baseline and yearly thereafter (~5y follow-up); Study beverage intake at baseline:; Baseline (svg/d), mean (SD): 0.11 (0.42); Outcomes Assessment Methods and Timing:; Height and weight: valid measure by study staff/BMI: calculated from height and weight. Waist circumference: measured in duplicate by trained staff (midway between lowest rib and iliac crest using anthropometric tape); average of two measures was analyzed value. Absolute change in body weight and WC: difference between yearly measured values and values from previous year; - Baseline and annually thereafter (mean follow-up 4.8y) | [underlined: Change in WC (cm) over 5y follow-up by concurrent changes in LNCSB intake (svg/d),] β (95% CI), generalized estimating equation; Overall: 0.15 (−0.09, 0.38), p=0.214; Men: 0.25 (−0.04, 0.53), p=0.096; Women: 0.00 (−0.37, 0.37), p=0.993; [underlined: Change in body weight (kg) over 5y follow-up by concurrent changes in LNCSB intake (svg/d),] β (95% CI), generalized estimating equation 0.10 (−0.05, 0.25), p=0.179 | Model adjustments:; - TEI: Yes (for food groups found to be significantly associated with outcomes); - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking, diet quality; - Other: Time (years, due to slight variations in period between successive visits), center, intervention group (combined MedDiets vs. control); for food groups for which the associations with changes in anthropometry were statistically significant, models were additionally adjusted for intake of other foods simultaneously, to estimate mutually adjusted associations. No multi-collinearity was observed between these food groups.; Limitations:; - Did not account for key confounders: race and/or ethnicity; - No preregistered data analysis plan; Limited generalizability; Funding:; CIBER Fisiopatología de la Obesidad y Nutrición (CIBEROBN); Instituto de Salud Carlos III (ISCIII); “FOLIUM” program within the FUTURMed project; Fundación Instituto de Investigación Sanitaria Illes Balears; ERC Advanced Research Grant
Ma, 2016^31^; PCS, Third Generation cohort of the Framingham Heart Study, U.S.; Analytic N=1,003; Participant characteristics at baseline: Adults in the Third Generation cohort of the Framingham Heart Study; - Age: Mean=45.3y; - Female: 45%; - Race and/or Ethnicity: 99.7% White; - SEP: NR; - Anthropometry: BMI ~27.4 kg/m2; - Physical activity: Score ~37.2; - Smoking: 9% Current smoker; - Diet quality: Whole grain intake (g/d): ~29 g/d Fruit intake: ~265 g/d; Vegetable intake: ~225 g/d SSB intake: ~3.7 servings/wk; - TEI: ~1900 kcal/d; Inclusion criteria: cohort members with CT scan at baseline (2002–2005) and follow-up (2008–2011); weight < 160 kg at first and second exams (due to CT machine's weight restrictions); age 35y (men) or 40y (women) at baseline (age for CT eligibility); Exclusion criteria: history of bariatric surgery, hard cardiovascular disease (stroke and myocardial infarction), or cancer (excluding non-melanotic skin cancer); missing data for SSB or diet soda (n=114); missing data on covariates at baseline (n=15) | Exposure: Diet soda intake (low-calorie cola; low-calorie, caffeine-free cola; other low-calorie carbonated beverage; “did not include all consumption of low calorie and artificially sweetened, noncarbonated beverages”); Other Exposures: SSB; Comparator: Diet soda intake (categorical): Non-consumers (none to <1 svg/mo): Median 0 svg/wk; Occasional consumers (1 svg/mo to <1 svg/wk):; Median 0.5 svg/wk; Frequent consumers (1 svg/wk to 1 svg/d): Median 3 svg/wk; Daily consumers (≥1 svg/d): 12 svg/wk; Exposure Assessment Methods and Timing:; Harvard semi-quantitative FFQ (validated); - Baseline; Study beverage intake at baseline: 50% Non-consumers, 13% Occasional consumers, 22% Frequent consumers, 15% Daily consumers; Outcomes Assessment Methods and Timing:; Height measured to nearest ¼ inch using vertical ruler; Weight measured with light clothes and rounded to nearest 0.5 pound. BMI calculated as kg/m2. Abdominal adiposity (visceral adipose tissue (VAT) and subcutaneous adipose tissue (SAT) measured by CT scan.; - Baseline (2002–2005), ~6y follow-up (2008–2011) | [underlined: Change in visceral adipose tissue], cm^3^, Linear regression, β (95% CI); Non-consumers: 680 (639, 722); Occasional consumers: 680 (599, 761); Frequent consumers: 737 (674, 799); Daily consumers: 725 (650, 801) P trend = 0.27; [underlined: Change in subcutaneous adipose tissue], cm^3^, Linear regression, β (95% CI); Non-consumers: 555 (511, 600); Occasional consumers: 616 (528, 703); Frequent consumers: 637 (570, 704); Daily consumers: 579 (497, 662) P trend = 0.72; [underlined: Weight], kg, Linear regression, β (95% CI); Change per frequency of Diet Soda intake:; Non-consumers: 2.8 (2.2, 3.3); Occasional consumers: 1.6 (0.5, 2.7); Frequent consumers: 1.7 (0.8, 2.5); Daily consumers: 2.7 (1.7, 3.8) P trend = 0.85; P interaction (Sex) = 0.01 P interaction (BMI) = 0.99; P interaction (T2DM) = 0.57; Men; Non-consumers: 2.5 (1.8, 3.2); Occasional consumers: 2.0 (0.5, 3.5); Frequent consumers: 2.8 (1.7, 4.0); Daily consumers: 3.7 (2.3, 5.0) P trend = 0.10; Women; Non-consumers: 3.3 (2.4, 4.2); Occasional consumers: 1.1 (−0.6, 2.7); Frequent consumers: 0.6 (−0.6, 1.8); Daily consumers: 1.5 (−0.1, 3.0) P trend = 0.11 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, diet quality (Saturated fat intake, SSB intake, whole grain, fruit, vegetable, coffee, nuts, and fish), smoking; - Other: Change in body weight (for change in VAT and SAT analyses); Limitations:; - Did not account for key confounders: socioeconomic position; - Follow-up time differs among participants; Exposure measured at baseline only; No preregistered data analysis plan; Funding:; NHLBI
Mozaffarian, 2011^35^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-Up Study (HPFS), US; Analytic N=NHS = 50,422; NHS II = 47,898; HPFS = 22,557; Participant characteristics at baseline: Adults; - Age: Mean (SD):; NHS 52.2y (7.2), NHS II 37.5y (4.1), HPFS 50.8y (7.5); - Female: NHS & NHS II: 100% HPFS: 0%; - Race and/or Ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: Mean (SD): BMI (kg/m2), NHS 23.7 (1.4), NHS II 23.0 (2.7), HPFS 24.7 (1.1); - Physical activity: MET-hr/wk, Mean (SD): NHS 14.8 (9.9), NHS II 21.6 (25.9), HPFS 22.9 (15.1); - Smoking: Never smoker: 53%, Past smoker: 33%, Current smoker: 13%, Missing: 1%; - Diet quality: Mean, serv/d Fruit: ~1.5; Vegetables: ~3.5 Whole grains: ~0.6; Additional food group data in paper; - TEI: NR; Exclusion criteria: obesity, diabetes cancer, or cardiovascular, pulmonary, renal, or liver disease at baseline; missing data on lifestyle habits; implausible energy intake, >9 blank responses on the diet questionnaire; newly pregnant during follow-up; >65y of age | Exposure: Diet soda intake (“low-calorie cola with caffeine”, “low-calorie caffeine-free cola”, and “other low-calorie beverages”); Other Exposures: Milk, SSB, 100% juice; Comparator: Continuous intake (svg/d); Exposure Assessment Methods and Timing:; Validated questionnaire; represents usual dietary intake; - At baseline, every 4y over 12- to 20-y follow-up; Study beverage intake at baseline: NR; Outcomes Assessment Methods and Timing:; Weight collected via self-report from questionnaire; - At baseline, and every 2y over 12- to 20-y follow-up | [underlined: Weight], lb, Linear regression, β (95% CI); Change per svg/d increase:; NHS: −0.04 (−0.10, 0.03), P=NS; NHS II: −0.10 (−0.17, −0.03), P<0.001; HPFS: −0.21 (−0.30, −0.12), P<0.001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, whole-fat and low-fat dairy, potato chips, potatoes/fries, whole grains, refined grains, sweets and desserts, processed and unprocessed meats, trans fat, fried foods at and away from home, and other beverage types); - Other: Alcohol, television watching, sleep duration; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Self-reported weight; Funding:; NIH; Searle Scholars Program
Nettleton, 2009^36^; PCS, Multi-Ethnic Study of Atherosclerosis (MESA), U.S.; Analytic N=2,428; Participant characteristics at baseline: Adults; - Age: Mean ~61y (45–84y); - Female: 53%; - Race and/or Ethnicity: 43% White, 23% African American, 21% Hispanic, 12% Chinese; - SEP: 85% High school degree; - Anthropometry: Mean BMI ~28 kg/m2; - Physical activity: Active leisure ~2650 MET-min/wk; - Smoking: 14% current smokers; - Diet quality: Food item, mean svg/d, by ASB intake category: rare or never, >rare/never but <1 serving/wk, ≥1 svg/wk to <1 svg/d, ≥1 svg/d; Whole grains: 0.56, 0.66, 0.66, 0.62 (P<0.001); Fruit: 1.8, 2.0, 1.9, 1.9 (P=0.04); Vegetables: 2.3, 2.4, 2.3, 2.3 (P=0.57); Salty snacks: 0.21, 0.22, 0.24, 0.22 (P=0.05); Processed meat: 0.18, 0.15, 0.16, 0.15 (P=0.004); - TEI: Mean ~1650 kcal/d; Inclusion criteria: Caucasian, African American, Hispanic, and Chinese adults, aged 45–84 years at baseline (2000–2002); Exclusion criteria: waist circumference ≥102 (men) or ≥88 cm (women) at baseline (for WC analysis) | Exposure: Diet soda intake (diet soda drinks, unsweetened mineral water); Other Exposures: SSB; Comparator: Diet soda intake (categorical): Rare/never (Median 0.0 svg/d); More than rare/never but <1 svg/wk (Median 0.1 svg/d); ≥1 svg/wk to <1 svg/d (Median 0.4 svg/d); ≥1 svg/d (Median 2.5 svg/d); Exposure Assessment Methods and Timing:; Validated FFQ; represents frequency and serving size; - Baseline (2000–2002); Study beverage intake at baseline:; Never, 59%; ≥1 svg/d, 14%; Outcomes Assessment Methods and Timing:; BMI calculated from measured weight in kg divided by square of height in meters.; Waist circumference (WC) measured at umbilicus using standard tape measure; high WC defined as ≥102 cm in men or ≥88 cm in wome; - Baseline (2000–2002), and three follow-ups (2002–2003, 2004–2005, 2005–2007) | [underlined: High WC], Cox proportional hazard, HR (95% CI); Rare/never (n=1544, ref) vs; >never to <1 svg/wk (n=208): 1.13 (0.82, 1.57); ≥1 svg/wk-<1 svg/d (n=602): 1.22 (0.95, 1.55); ≥ 1 svg/d (n=449): 1.59 (1.23, 2.07); When adjusting for baseline WC:; Rare/never (ref) vs; ≥ 1 svg/d: 1.18 (0.96, 1.44) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position (education), anthropometry at baseline (WC and BMI), physical activity, smoking, diet quality (food intakes (svg/d of whole grain bread/rice/cereal/pasta, nuts/seeds, fruit, vegetables, white potatoes, refined grain bread/rice/cereal/pasta, salty snacks, desserts, red meat, processed meat, high-fat dairy products, low-fat dairy products, SSB, and coffee) or nutrient intakes (fiber, calcium, phosphorus, potassium, magnesium, and sodium)). "Adjustment for these dietary factors did not markedly change risk estimates" (data not shown); - Other: Study site, regular dietary supplement use, change in WC or body weight; Limitations:; - Did not account for key confounders:; - Exposure data only measured at baseline; Exposure not well-defined; No preregistered data analysis plan; Funding:; NHLBI
Pan, 2013^37^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-up Study (HPFS), U.S.; Analytic N=NHS = 50,013 NHS II = 52,987; HPFS = 21,988; Participant characteristics at baseline: Adults; - Age: Mean ~47y; - Female: NHS & NHS II: 100%; HPFS: 0%; - Race and/or Ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: Overweight: 31%, Obesity: 17%, BMI Mean: ~25 kg/m2; - Physical activity: Mean~18 MET-hr/wk; - Smoking: Never smoker: 54%, Past smoker: 33%, Current smoker: 13%; - Diet quality: Mean, serv/d SSB: ~0.4; - TEI: NR | Exposure: Diet beverage intake (“low-calorie cola with caffeine”, “low-calorie caffeine-free cola”, and “other low-calorie beverages”); Other Exposures: 100% juice, SSB, LNCSB, Coffee/Tea; Comparator: Continuous intake (serv/d); Exposure Assessment Methods and Timing:; Validated FFQ; represents usual intake of foods and beverages; - At baseline, every 4y over 16- to 20-y follow-up; Study beverage intake at baseline: Diet beverage intake, svg/d, Mean (5th-95th%):; NHS 0.52 (0–2.5), NHS II 1.06 (0–4.5), HPFS 0.51 (0–2.5); Outcomes Assessment Methods and Timing:; Weight was collected via self-report from questionnaire; - At baseline, and every 2y over 16- to 20-y follow-up | [underlined: Weight change over each 4y period], kg, Linear regression, β (95% CI); Change per svg/d increase:; NHS: −0.11 (−0.15, −0.08); NHS II: −0.07 (−0.10, −0.03); HPFS: −0.14 (−0.18, −0.09); Stratified by age: ≤50y, >50y; NHS: −0.19 (−0.26, −0.12), 0.13 (0.09, 0.18), P<0.001; NHS II: −0.09 (−0.13, −0.06), 0.13 (0.04, 0.22), P<0.001; HPFS: −0.17 (−0.25, −0.09), −0.12 (−0.18, −0.06), P=0.07; Stratified by BMI (kg/m2): <25, 25–29.9, ≥30; NHS: −0.02 (−0.07, 0.02), −0.13 (−0.20, −0.07), −0.23 (−0.34, −0.12), P<0.001; NHS II: 0.00 (−0.03, 0.04), −0.11 (−0.17, −0.05), −0.07 (−0.16, 0.02), P=0.09; HPFS: −0.02 (−0.08, 0.04), −0.14 (−0.21, −0.08), −0.26 (−0.44, −0.08), P<0.001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, whole grain, refined grain, potatoes, potato chips, red meat, other dairy products, sweets and deserts, nuts, fried foods, and trans fat, and other beverage types); - Other: Alcohol, protein, television watching; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Self-reported weight; Funding:; NIH
Qi, 2012^40^; PCS, Nurses Health Study (NHS) + Health Professionals Follow-Up Study (HPFS) + Women’s Genome Health Study (WGHS), U.S.; Analytic N=NHS: Analytic N=6934; HPFS: Analytic N=4423; WGHS: Analytic N=21740; Participant characteristics at baseline: Adults; - Age: Mean~51y; - Female: 87%; - Race and/or Ethnicity: 100% European ancestry; - SEP: Occupation: 100% health professionals; - Anthropometry: BMI: Mean~25 kg/m2; - Physical activity: Mean~16 MET-hr/wk; - Smoking: Current smoker ~9%; - Diet quality: Alternative Healthy Eating Index (AHEI) score:; NHS: ~28; HPFS: ~43; - TEI: ~1700 kcal/d; Inclusion criteria:; NHS: female registered nurses, 34 to 59y at baseline (1980), European ancestry; HPFS: male health professionals 40 to 75y at baseline (1986); genotype data based on GWAS available; European ancestry; WGHS: initially healthy female health professionals 45y or older at baseline (1992–1995), no major chronic diseases at baseline, confirmed self-reported European ancestry, available genotype data and responses to FFQ, no diabetes at baseline; Exclusion criterion: obesity at baseline | Exposure: Artificially sweetened beverage intake (caffeinated, caffeine-free, and noncarbonated low-calorie beverages); Other Exposures: SSB; Comparator: Artificially sweetened beverage intake (categorical; servings): <1 svg/mo, 1–4 svg/mo, 2–6 svg/wk, ≥1 svg/d; Exposure Assessment Methods and Timing:; Validated semi quantitative FFQ; - At baseline, and every 4y after for NHS and HPFS; At baseline only for WGHS; Study beverage intake at baseline: NHS:; ~0.4 svg/d; HPFS: ~0.5 svg/d; WGHS: ~0.8 svg/d; Outcomes Assessment Methods and Timing:; Height and weight were self-reported and highly correlated (0.97) with measured values in a sub-sample; BMI calculated as kg/m2. Obesity (BMI>30 kg/m2); - NHS: At baseline, and every 4y follow-up assessment up to 18y; HPFS: At baseline, and every 4y follow-up assessment up to 12y; WGHS: At baseline, and 6y follow-up | Data represent the difference in BMI for each increment of 10 risk alleles, stratified by beverage intake. P for interaction (genetic predisposition score*beverage intake); [underlined: Increase in BMI, per increment of 10 risk alleles], Linear regression, β (SE); NHS (n=6934); <1 svg/mo: 1.42 (0.18); 1–4 svg/mo: 1.25 (0.21); 2–6 svg/wk: 1.39 (0.20); ≥1 svg/d: 1.36 (0.27); P for interaction = 0.91; HPFS (n=4432); <1 svg/mo: 0.95 (0.18); 1–4 svg/mo: 0.76 (0.23); 2–6 svg/wk: 0.45 (0.20); ≥1 svg/d: 0.92 (0.29); P for interaction = 0.46; WGHS (n=21,740); <1 svg/mo: 1.60 (0.15); 1–4 svg/mo: 1.43 (0.25); 2–6 svg/wk: 1.46 (0.16); ≥1 svg/d: 1.63 (0.18); P for interaction = 0.81 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, diet quality (AHEI score, for NHS and HPFS), smoking; - Other: Source of genotyping data or eigenvectors derived from GWAS, time spent watching television (for NHS and HPFS), geographic region (for WGHS); Limitations:; - Did not account for key confounders: socioeconomic position; - Weight and height self-reported; No preregistered data analysis plan; Funding:; NIH; Merck Research Laboratories; American Heart Association; Harvard Glaucoma Center of Excellence; Amgen
Schulze, 2004^41^; PCS, Nurses’ Health Study II, U.S.; Analytic N=51,603; Participant characteristics at baseline: Adult female nurses; - Age: Mean ~36y (24–44y); - Female: 100%; - Race and/or Ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~24.4 kg/m2; - Physical activity: ~19 METs/wk; - Smoking: 12% current smokers; - Diet quality: Cereal fiber: ~5.5 g/d; Total fat intake: ~31% of total energy intake; - TEI: Mean ~1800 kcal/d; Inclusion criteria: female nurses aged 24 to 44y at study initiation (1989); Exclusion criteria: missing dietary questionnaire in 1991 or >9 items on FFQ left blank; implausible total energy intake (< 500 kcal/d or >3500 kcal/d); history of diabetes, cancer (except nonmelanoma skin cancer), or CVD at baseline; no data on physical activity in 1991 questionnaire, missing SSB intake information, history of diabetes or CVD before 1995 or reported cancer diagnosis (except nonmelanoma skin cancer) on any questionnaire, missing body weight information, no data on physical activity assessed in 1997. | Exposure: Diet soft drinks (low-calorie cola with caffeine, low-calorie caffeine-free cola, and other low-calorie beverages); Other Exposures: SSB, 100% juice; Comparator: Diet soft drink intake (categorical; change in drink frequency from 1991 to 1995): Consistent ≤1/wk, Consistent ≥1/d, Increased (≤1/wk to ≥1/d), Decreased (≥1/d to ≤1/wk), Other; Exposure Assessment Methods and Timing:; Validated semi-quantitative FFQ; represents intake over previous year; - Baseline (1991), 4y follow-up (1995); Study beverage intake at baseline: NR; Outcomes Assessment Methods and Timing:; Height measured via self-report at baseline only, Weight measured via self-report. BMI calculated as kg/m2; - Baseline (1991), 4y follow-up (1995) | [underlined: Weight gain,] Per change in diet soft drink consumption from 1991–1995:; Increased intake (≤1/wk to ≥1/d): 1.59 kg; Decreased intake (≥1/d to ≤1/wk): 4.25 kg; P<0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, diet quality (cereal fiber intake, total fat intake), smoking; - Other: Postmenopausal hormone use, oral contraceptive use; Limitations:; - Did not account for key confounders: race and/or ethnicity, socioeconomic position; - Attrition 56% without information on non-completers; Weight and height self-reported; No preregistered data analysis plan; Funding:; NIH; European Association for the Study of Diabetes/American Diabetes Association; German Academic Exchange Service (DAAD)
Stern, 2017^42^; PCS, Mexican Teachers’ Cohort, Mexico; Analytic N=11,218 (weight) and 9,294 for WC; Participant characteristics at baseline:; Female teachers; - Age: Mean (SD): 43.3 (5.2) y; Range 25–64y; - Female: 100%; - Race and/or Ethnicity: 100% Hispanic; - SEP: NR; - Anthropometry: Mean BMI: 27.2 (4.4) kg/m2; 42% with overweight, 23% with obesity; - Physical activity: High 34%, Medium 37%, Low 29%; - Smoking: Never 81%, Current 8%; - Diet quality: svg/wk, mean (SD) Fruit: 19.3 (15.0); Vegetables: 24.6 (17.2); Homemade sweetened beverages: 10.6 (11.0); - TEI: Mean (SD): 1756 (614) kcal/d; Inclusion criteria: Female teachers age 25y or older at baseline; completion of baseline and follow-up questionnaire; Exclusion criteria: diabetes, cancer, or heart disease at baseline (n = 1481); age ≥65y; inadequate dietary information in either 2006 or 2008 (energy intake < 500 or > 3500 kcal/day, response to ≤ 70 items on the dietary questionnaire, or missing cereal section); missing information on soda consumption in either 2006 or 2008; missing height or weight data | Exposure: Sugar-free soda; Other Exposures: SSB; Comparator: Sugar-free soda intake (continuous; svg/d); Sugar-free soda intake (categorical; svg/mo): Decreased (<-1 svg/mo), No change (−1 to +1 svg/mo), Increased (>1 svg/mo; Exposure Assessment Methods and Timing:; Validated semi-quantitative FFQ; represents intake over previous year; - Baseline (2006), 2008; Study beverage intake at baseline: Mean (SD): 0.1 (0.1) svg/wk; Outcomes Assessment Methods and Timing:; Height (in cm) and weight (in kg) were self-reported; Waist circumference (WC, in cm) was self-reported; participants were provided a plastic measuring tape and instructions to assess their WC; - Baseline (2006), 2008 | [underlined: WC], cm, change from 2006–2008, Linear regression, β (95% CI); Per 1 svg/d increase: −2.7 (−5.2, −0.1), P=0.04; Per change in svg/mo:; No change (−1 to +1, n=6220): Ref; Decreased (<1, n=1856): −0.1 (−0.5, 0.3); Increased (>1, n=1218): −0.7 (−1.1, −0.3); [underlined: Weight], kg, Change from 2006–2008, Linear regression, β (95% CI); Per 1 svg/d increase: 0.0 (−1.3, 1.4), P=0.98; Per change in svg/mo:; No change (−1 to +1, n=7437): Ref; Decreased (<1, n=2270): −0.1 (−0.3, 0.1); Increased (>1, n=1511): −0.2 (−0.4, 0.0) | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, anthropometry at baseline, physical activity, diet quality (food and beverage intake (red meat, dairy, yogurt, fruit, vegetables, nuts, white bread, flour tortillas, corn tortillas, orange or grapefruit juice, SSB, and homemade sweetened beverages)), smoking; - Other: State of residency, oral contraceptive use, menopausal status, postmenopausal hormone therapy use; Limitations:; - Did not account for key confounders: socioeconomic position; - Attrition 60% without information on non-completers; Weight, height, and waist circumference self-reported; No preregistered data analysis plan; Funding:; AstraZeneca; Bloomberg Philanthropies (National Institute of Public Health in Mexico); Bernard Lown Scholars Program in Cardiovascular Health; American Institute of Cancer Research; Consejo Nacional de Ciencia y Tecnología; NIH

b Abbreviations: AHA: American Heart Association; AI/AN: American Indian and Alaska Native; ANOVA: analysis of variance; ANCOVA: analysis of covariance; ASB: artificial/artificially sweetened beverage; BMI: body mass index; BMIZ: BMI z-score; CDC: Centers for Disease Control and Prevention; CI: confidence interval; cm: centimeter; CT: computed tomography; CTSA: Clinical and Translational Science Awards; CVD: cardiovascular disease; d: day; DB: diet beverage; DEXA/DXA: dual energy x-ray absorptiometry; EER: estimated energy requirement; EI: energy intake; EU: exercise units; FFQ: food frequency questionnaire; fl oz: fluid ounces; g: grams; HbA1c: hemoglobin A1c; HDL: high-density lipoprotein cholesterol; HHS: Department of Health and Human Services; HOMA-IR: Homeostatic Model Assessment for Insulin Resistance; HPFS: Health Professionals Follow-up Study; HR: hazard ratio; IPR: incidence proportion ratio; ITT: intention to treat; kg: kilogram; kJ: kilojoules; L: liter; LDL: low-density lipoprotein cholesterol; LNCSB: low- and no-calorie sweetened beverages; M: meter; MET: metabolic equivalent of task; mL: milliliter; mmHg: millimeters of mercury; mo: month; NCI: National Cancer Institute; NCRR: National Center for Research Resources; NHLBI: National Heart, Lung, and Blood Institute; NHS: Nurses’ Health Study; NHS II: Nurses’ Health Study II; NIA: National Institute on Aging; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NNS: non-nutritive sweetener; NR: not reported; NS: not significant; OR: odds ratio; Oz: ounce; PCS: prospective cohort study; PREDIMED: Prevención con Dieta Mediterránea; RCT: randomized controlled trial; Ref: reference; RR: relative risk; SAAT: subcutaneous abdominal adipose tissue; SAT: subcutaneous adipose tissue; SD: standard deviation; SE: standard error; SEP: socioeconomic position; SSB: sugar sweetened beverages; svg: serving; T2D: type 2 diabetes; TEI: total energy intake; UNC-CH: University of North Carolina-Chapel Hill; USDA: United States Department of Agriculture; VAT: visceral adipose tissue; WC: waist circumference; WGHS: Women’s Genome Health Study; Wk: week; wt: weight; y: year(s)

Table 12 Risk of bias for randomized controlled trials examining LNCSB consumption in adults and body composition and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bonnet, 2018 ^20^ | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | HIGH
Madjd, 2015 ^32^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Madjd, 2018 ^33^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Maersk, 2012 ^34^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Peters, 2014 ^38^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Peters, 2016 ^39^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS
Tate, 2012 ^43^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Vazquez-Duran, 2016 ^44^ | LOW | LOW | LOW | LOW | LOW | LOW

a Possible ratings of low, some concerns, or high determined using the [underlined: "Cochrane Risk-of-bias 2.0" (RoB 2.0)] (August 2019 version)” Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 13 Risk of bias for observational studies examining LNCSB consumption in adults and body composition and risk of obesity^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Bes-Rastrollo, 2006 ^18^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Bes-Rastrollo, 2008 ^19^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Buso, 2022 ^21^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Chen, 2009 ^22^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Duffey, 2012 ^23^ | LOW | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Ferreira-Pego, 2016 ^24^ | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Fowler, 2008 ^26^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Fowler, 2015 ^25^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Garduno-Alanis, 2020 ^27^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Gearon, 2018 ^28^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hinkle, 2019 ^29^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Konieczna, 2019 ^30^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Ma, 2016 ^31^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Mozaffarian, 2011 ^35^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Nettleton, 2009 ^36^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Pan, 2013 ^37^ | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Qi, 2012 ^40^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Schulze, 2004 ^41^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Stern, 2017 ^42^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 14 Evidence examining the relationship between LNCSB consumption during postpartum and postpartum weight change^a^

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcome(s) | Results | Confounding and Study Limitations
Davis, 2017^45^; PCS, Study of Women, Infant Feeding and Type 2 Diabetes After GDM Pregnancy (SWIFT), U.S.; Analytic N=888; Participant characteristics at baseline: Postpartum women with history of gestational diabetes; - Age: Mean (SD), 32.6 (4.8)y; - Female: 100%; - Race and/or Ethnicity: Non-Hispanic White: 24.1%; Non-Hispanic Black: 7.7%; Asian: 37.1%; Native American: NR; Hispanic: 29.3%; Other: 1.9%; - SEP: Education: High school or less: 23.3%, Some college: 27.6%, ≥4y of college: 49.1%; - Anthropometry: Pre-pregnancy BMI: Mean (SD), 29.4 (7.1) kg/m2; - Physical activity: Total physical activity (PA), mean (SD): 46.1 (21.1) MET-hr/wk; Moderate to vigorous PA, mean (SD): 24.7 (15.4) MET-hr/wk; - Smoking: NR; - Diet quality: Whole egg consumption: ≥5 svg/wk: 20.1%; 2–4 svg/wk: 40%; 1 svg/wk: 22.1%; None: 17.6% Processed meats (sausages, salami, bologna, hot dogs, bacon): ≥5 svg/wk: 5.3%; 2–4 svg/wk: 27.9%; 1 svg/wk: 27.7%; None: 38.9%; Fried foods (fried chicken, fish, seafood, french fries, onion rings): ≥5 svg/wk: 3.6%; 2–4 svg/wk: 23.4%; 1 svg/wk: 39.8%; None: 33.2% fried food; eggs; processed meats; - TEI: Mean (SD), 834.2 (340.9) kcal/d; Inclusion criteria: women with GDM pregnancy who delivered singleton, live birth ≥35wks of gestation, 20–45y, and no history of diabetes; residence in northern California; Exclusion criteria: participants with elevated fasting glucose ≥126 mg/dL, 2hr glucose ≥200 mg/dL at 6–9wk postpartum diagnostic of diabetes, infant born <35 weeks gestation, missing beverage intake at baseline, missing 1yr postpartum body weight measurements, and missing dietary intake at baseline or glucose tolerance status at 1yr follow-up. | Exposure: Diet soda (with and without caffeine); Other exposures: SSB; Comparator: Categorical, svg/wk None (n=622); <1 (n=129); ≥2 (n=130); [underlined: Exposure assessment method and timing]:; - 13-item Caffeine Questionnaire; medium serving size = 12-oz can; participants reported usual serving size as small, medium, or large; - At baseline (6–9 wk postpartum); Study beverage intake at baseline:; ≥2 svg/wk: 13.9%; ≤1 svg/wk: 14.8%; None: 70.7%; Outcomes and assessment methods:; - Pre-pregnancy weight was self-reported and validated with measurements within 1yr prior to pregnancy. Weight measured (to nearest 0.1 lb) at 6–9wk gestation and 1yr postpartum using a calibrated digital scale. Height measured (to nearest cm) using a stadiometer. Gestational weight gain categories for pre-pregnancy BMI determined by IOM. Postpartum weight retention calculated by subtracting pre-pregnancy weight from weight at 1yr postpartum. Substantial postpartum weight retention (SPWR) defined as ≥5kg weight retention at 1yr postpartum; - At baseline (pre-pregnancy), 6–9wk postpartum, and 1yr postpartum | [underlined: 1y Postpartum weight retention], < 5kg weight retention (n=690) vs. ≥5kg weight retention (n=198), Chi-square test; ≥2 svg/wk: 13.9% vs. 17.2%; <1 svg/wk: 14.8% vs. 13.6%; None: 70.7% vs. 67.7% P=0.37 | Model adjustments:; - TEI: no; - Key confounders: none; - Other: N/A; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, diet quality, physical activity, smoking, parity, human milk feeding; - Exposure data only measured at baseline; - No information on non-completers; Funding:; NICHD; NCRR

a Abbreviations: BMI: body mass index; GDM: gestational diabetes mellitus; IOM: Institute of Medicine; LNCSB: low- and no-calorie sweetened beverages; N/A: not applicable; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Human Development; NCRR: National Center for Research Resources; NR: not reported; PCS: prospective cohort study; SD: standard deviation; SEP: socioeconomic position; SSB: sugar-sweetened beverages; TEI: total energy intake

Table 15 Risk of bias for observational studies examining LNCSB consumption during postpartum and postpartum weight change^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Davis, 2017^45^ | VERY HIGH | LOW | LOW | LOW | HIGH | LOW | LOW | VERY HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.