# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 5 systematic reviews assessing the relationship between beverage consumption (LNCSB, dairy milk and milk alternatives^†^; beverage patterns^‡^; 100% juice^§^; and sugar-sweetened beverages^**^) and growth, body composition, and risk of obesity. The literature search (Appendix 4) yielded 36,223 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 33,121 titles, 2,552 abstracts, and 463 full-text articles. Reasons for full-text exclusion are in Appendix 5. No additional articles with data on LNCSB and relevant outcomes were identified from the manual search. In total, the body of evidence examining LNCSB included 45 articles:

- [underlined: Children and adolescents]: 17 articles^1–17^
- [underlined: Adults and older adults]: 27 articles^18–44^
- [underlined: Individuals during pregnancy and postpartum]: 1 article^45^

† Raynor HA, Deierlein AL, Gardner CD, . Dairy Milk and Milk Alternatives and Growth, Body Composition, and Risk of Obesity: A Systematic Review U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR03

‡ Raynor HA, Deierlein AL, Gardner CD, . Beverage Patterns and Growth, Body Composition, and Risk of Obesity: A Systematic Review U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review; 2025. 10.52570/NESR.DGAC2025.SR02

§ Deierlein AL, Raynor, HA, Andres A, . 100% Juice and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review Available at: 10.52570/NESR.DGAC2025.SR05

** Deierlein AL, Raynor HA, Andres A, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR23

Figure 2 Literature search and screen flowchart

The literature searches in PubMed, Embase, Cochrane, and CINAHL, retrieved 36,223 records after removing duplicates. 167 were included from existing reviews. 38 were found with manual search methods. 33,121 titles, 2,552 abstracts, and 463 full-texts were excluded. 292 articles were included across the systematic reviews examining beverage consumption and growth, body composition, and risk of obesity.

## Children and adolescents

### Description of the evidence

The body of evidence examining the relationship between LNCSB consumption and growth, body composition, and risk of obesity in children and adolescents included 17 articles. Evidence for this population is summarized in Table 9 and risk of bias assessments for each article are detailed in Table 10.

#### Population

Of the 17 articles in children and adolescents, all were prospective cohort studies (PCS) with sample sizes ranging from n=42 to n=11,634 participants. Most studies were from the United States; however, there were also studies from Australia,^16^ Denmark,^17^ and the United Kingdom.^^4,8,12^^ Most studies did not base eligibility on weight status, although one included only participants without – but at risk for – overweight or obesity^17^ and one study was in participants with overweight or obesity.^3^

Twelve articles were in children (mean age range: 2.9 to 12 years at baseline), while 5 were in adolescents (mean age range: 12.8 to 16 years at baseline). Lengths of follow-up ranged from 6 months to 12 years. Six of the 17 articles did not report race and/or ethnicity data, and 7 did not report information on socioeconomic position (SEP). Of those that did provide information on race and/or ethnicity, 8 articles were from studies in predominantly white populations, 1 article was from a study in a 100% Hispanic population, 1 reported that >50% of participants were Black, and 1 stated that the population was >50% racial and/or ethnic minorities. Six articles were from studies conducted in middle- to higher-SEP populations, while 4 articles were from studies conducted in lower-SEP populations. Two articles from observational studies^^1,7^^ reported receiving industry funding; funding sources for all articles are reported in Table 9.

#### Exposure

Baseline intake of LNCSB in these study populations was low and definitions of LNCSB varied considerably between articles: some assessed diet soda intake alone^^1,2,5,6,9,11,13–15^^ while others defined the category more broadly to include beverage types such as fruit drinks, coffee, or tea with low- and no-calorie sweeteners.^^3,4,7,8,10,12,16,17^^ Ten articles assessed LNCSB intake through dietary recalls ^^2–4,7–10,14,16,17^^, while 6 used food frequency questionnaires^^1,5,6,11,13,15^^ and 1 collected exposure data via parent interview.^12^

#### Comparator

Most studies compared LNCSB continuously, although some studies categorically compared different intake levels of LNCSB (e.g., tertiles of LNCSB intake per week). No studies compared LNCSB intake to water. Studies that compare LNCSB to sugar sweetened beverages (SSB) were not included in this systematic review; they are included in the systematic review assessing the relationship between SSB and growth, body composition, and risk of obesity.^*^ The units used to measure LNCSB intake varied across articles (e.g., grams, ounces, servings), as did the time scale for consumption (e.g., intake per day, week, or month). These variations, while not insurmountable to normalize, complicated the comparison of results from different articles.

* Deierlein AL, Raynor HA, Andres A, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR23

#### Outcomes

Seven articles reported growth outcomes (e.g., BMI z-score),^^2–4,9,13,16,17^^ 6 reported body composition outcomes (e.g., percent body fat, waist circumference),^^3,7–10,16^^ and 10 included risk of obesity outcomes (e.g., incidence of overweight, obesity).^^1,5–7,10–15^^ Four articles with adolescent populations included outcomes based on self-reported height and weight, which was used to calculate BMI^^1,5,15^^ or prevalence and incidence of overweight.^6^ All other articles reported outcomes measured by study personnel.

### Synthesis of the evidence

Articles in children and adolescent populations were synthesized together. Since energy intake is an important covariate when interpreting studies on the relationship between LNCSB consumption and growth, body composition and risk of obesity, articles were organized by whether or not they adjusted for total energy intake (TEI). Both approaches were considered within the evidence synthesis. Thirteen studies adjusted for TEI, with 5 of these presenting both adjusted and unadjusted results. With the exception of one article,^16^ adjusting for TEI did not change the statistical significance of the findings. Four articles did not adjust for TEI.^^4,5,12,15^^

Most articles (11 of 17) reported null findings in the association between LNCSB and growth, body composition and risk of obesity outcomes. Among articles with statistically significant findings, there were more direct associations than indirect associations; however, there were concerns including lack of adjustment for age and sex in BMI outcomes, small sample sizes, and low overall intake of LNCSB that made the available results more challenging to interpret.

#### Growth Outcomes

All but one article with growth outcomes, such as weight or BMI z-score, reported null results. One study found that LNCSB consumption at 8 years of age was significantly associated with decreases in BMI z-scores at 11.5 years of age, when TEI was both adjusted and unadjusted for in the model.^16^

#### Body Composition Outcomes

Most articles with body composition measures, such as waist circumference or body fat percentage, found no association between LNCSB intake and the outcome of interest. One study found no association between diet soda intake from 3–5 years of age with waist circumference at 5–6 years of age.^9^ One study found no association with changes in percent body fat in adolescents;^10^ similarly, Davis et al^3^ did not find an association between LNCSB intake and body fat percentage in Hispanic adolescents with overweight or obesity. One study in children ages 3–5 years at baseline found no association between unsweetened or diet beverages and body fat percentage, waist circumference or sum of skinfolds over 12 years of follow-up; median baseline intake of LNCSB was reported as 0.0 ounces per day.^7^ Johnson et al^8^ reported an association between low-energy beverage intake and increased fat mass from 5 to 9 years and higher fat mass index quintile at 9 years; however, the fat mass index quintile findings were explained by overweight status at ages 5 and 7 years. Zheng et al^16^ found a statistically significant association between diet drink intake at 8 years of age and lower body fat percentage after 11.5 years of age; however, this relationship was only significant when TEI was adjusted for.

#### Risk of Obesity Outcomes

Three articles reported results on the incidence or prevalence of overweight or obesity. One found that, in adolescent girls, higher baseline intake of LNCSB was associated with greater prevalence and incidence of overweight 5 years later; however, there was no association with change in LNCSB intake for prevalence or incidence of overweight. In this same article, baseline intake of LNCSB by adolescent boys was not associated with either prevalence or incidence of overweight 5 years later; however, a greater increase in intake of LNCSB was significantly associated with prevalence of overweight after 5 years, but not with incident overweight.^6^ Another study found that consuming LNCSB 1 to 6 times a week compared with no consumption at age 4–5 years was significantly associated with greater risk of obesity at age 7–8 years; however, this did not follow a linear pattern and there was no association between LNCSB intake at age 4–5 years and risk of overweight at age 7–8 years.^12^ The third study found that, in school-aged children (mean age 12 years), baseline intake of LNCSB was not associated with obesity, but increased consumption was associated with lower risk of obesity 19 months later.^11^

Nine articles reported results on BMI. Five of the 9 articles did not adjust for age or sex,^^1,5,7,10,14^^ which limits the ability to practically interpret the results in these study populations. Of those that did adjust for age and sex,^^11–13,15^^ none reported an association between LNCSB intake and BMI or change in BMI. LNCSB intake in these study participants was low (2 articles reported a majority with no or <1 serving per week; 1 article reported mean baseline intake of <1 ounce per day) or not reported. Overall, adjusting for TEI in analyses of LNCSB and risk of obesity outcomes did not seem to change the statistical significance of the results.

Based on these studies, limited evidence suggests that LNCSB consumption by children and adolescents may not be associated with growth, body composition, and risk of obesity.

### Conclusion statement and grade

The Committee developed and graded a conclusion statement for the systematic review question: “What is the relationship between low- and no-calorie sweetened beverage consumption and growth, body composition, and risk of obesity?” based on their review of evidence in children and adolescents (see Table 5).

Table 5 Conclusion statement and grade for LNCSB and growth, body composition, and risk of obesity in children and adolescents

Conclusion Statement | Low- and no-calorie sweetened beverage consumption by children and adolescents may not be associated with growth, body composition, and risk of obesity. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 17 prospective cohort studies
Consistency | Substantial concerns with variation in the direction of findings
Precision | Some concerns due to small sample sizes and varying metrics across studies
Risk of bias | Substantial concerns, particularly risk of bias due to confounding and missing data
Directness | Some concerns with directness, given lack of RCT data
Generalizability | Some concerns with applicability to the U.S. population due to low reported racial and/or ethnic diversity

#### Assessment of the evidence

The body of evidence underlying the conclusion statement includes 17 PCS, and the evidence was graded based on an assessment of 5 grading elements, as described below. In addition, publication bias was also a consideration; however, it was not deemed a serious concern for this body of evidence because multiple studies reported only nonsignificant findings while others reported significant findings or a mix of significant and nonsignificant.

##### Consistency

The direction of findings varied across articles. Most demonstrated null results, and those that had statistically significant findings varied between unfavorable and beneficial effects on outcomes.

##### Precision

There were some concerns with precision due to small sample sizes, low intake of LNCSB in most study populations, and varying metrics across studies.

##### Risk of bias

Risk of bias assessments for each article are detailed in Table 10. Only 1 of the 17 articles accounted for all key confounders. There were substantial concerns due to missing data (large study cohorts with high attrition or exclusion) and selection of the reported results, as most articles did not have a predefined data analysis plan.

##### Directness

Most studies were designed to directly measure and analyze the relationship between LNCSB intake and outcomes related to growth, body composition, and risk of obesity. However, a lack of data from RCTs limited directness.

##### Generalizability

Over 70% of the included articles (12 of 17) were conducted within the United States. The age distribution of study participants spanned from 2.9 to 16 years of age, with the continuum of the age range represented across articles. However, there was low reported racial and/or ethnic diversity among study populations, limiting the generalizability of the available evidence.

## Adults and older adults

### Description of the evidence

Evidence for consumption of LNCSB in adults and body composition and risk of obesity is summarized in Table 11.

#### Population

Of the 27 articles, 8 were from RCTs and 19 were from PCS. Most studies were conducted within the United States,^^19,22,23,25,26,31,35–41,43^^ though studies from Spain,^^18,24,30^^ Denmark,^^29,34^^ Iran,^^32,33^^ Mexico,^^42,44^^ Australia,^28^ France,^20^ the Netherlands,^21^ and Russia^27^ were also included. Five RCT articles^^20,34,38,39,43^^ and 3 articles from observational studies^^29,40,42^^ reported receiving industry funding; funding sources for all articles are reported in Table 11.

The 8 RCT articles^^20,32–34,38,39,43,44^^ were from 6 studies with a mean baseline age ranging from 22 to 48 years. All articles enrolled >50% females, with 6 articles enrolling >80% females. Six articles had inclusion criteria for BMI ≥25 kg/m^2^ and 5 articles required participants to be habitual LNCSB consumers at baseline. Two articles were from a trial conducted in a predominantly white population and 1 article reported that >50% participants were Black; the remaining 5 articles did not report race and/or ethnicity data. One RCT was conducted in a higher-SEP population; the other 7 articles did not report SEP data.

The 19 PCS articles^^18,19,21–31,35–37,40–42^^ were from 17 independent cohorts with a mean baseline age ranging from 25 to 69 years. All but one of the cohorts was >50% female, and sample sizes ranged from n=466 to n=78,286. Six articles were from studies conducted in predominantly white populations, 2 articles were from studies enrolling >50% Mexican Americans, 1 article had a 100% Hispanic population, 1 article reported that participants were predominantly Black, and 1 article reported that participants consisted of >50% racial and/or ethnic minorities. Eight of the 19 articles did not report race and/or ethnicity information. Eight articles were from studies in middle- to high-SEP populations, 5 articles were from studies with lower-SEP populations, and 6 articles did not report SEP information.

#### Intervention/exposure and comparators

##### Randomized Controlled Trials

In the RCTs, LNCSB as the intervention was compared to either water, unsweetened beverages (water, unsweetened coffee, and tea), or an attention control group who maintained usual beverage intake. Studies that compared LNCSB to SSB were not included in this systematic review; they are included in the systematic review assessing the relationship between SSB and growth, body composition, and risk of obesity.^*^ One RCT was a crossover trial in which participants consumed 660 milliliters (mL) daily of LNCSB or carbonated water for 12 weeks in each arm.^^20^^ Another RCT was a 24-week weight loss trial with a 1-year maintenance phase conducted in women with overweight or obesity who were habitual consumers of diet beverages; one group of participants continued their usual LNCSB intake by drinking 250 mL after lunch 5 days a week, and another group substituted 250 mL water for LNCSB.^^32,33^^ Vazquez-Duran et al^^44^^ conducted an RCT in which Mexican nursing students were divided into three arms of using LNCSB, SSB or no intervention for 6 months. For LNCSB, the intervention group was permitted to drink only beverages with non-caloric sweeteners and plain water, and the comparator group was not permitted to drink sweetened beverages. In a 6-month trial, Maersk et al^^34^^ compared diet cola consumption (1 liter per day) to the same amount of still water. In another 6-month trial, Tate et al^^43^^ randomized participants to either replace at least 2 servings (≥200 kcal) per day of caloric beverages with diet beverages, to replace the same amount of caloric beverages with water, or to an “attention control” group, who received equal contact time and attention but no instruction to change beverage intake. The final RCT was a 12-week weight loss trial with a 40-week maintenance phase conducted in adults with overweight or obesity with habitual intake of LNCSB.^^38,39^^ In this study, the intervention group consumed at least 710 mL daily of LNCSB, with unrestricted water consumption; the comparator group consumed at least 710 mL daily of water and refrained from LNCSB consumption.

* Deierlein AL, Raynor HA, Andres A, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR23

##### Prospective Cohort Studies

In the PCS articles, definitions of LNCSB varied: some articles assessed diet soda intake alone^^18,19,21,25,27,28,31,42^^ while others defined the category more broadly, including beverages such as low- and no-calorie sweetened coffee, tea, or diet/light lemonade.^^22–24,26,29,30,35–37,40,41^^ All but one article^^22^^ evaluated LNCSB intake with food frequency questionnaires.

Most articles (12 of 19) compared LNCSB intake categorically, grouping participants by amount of LNCSB consumed in a given time frame (e.g., servings per month) or by change in consumption habits over the follow-up time frame (e.g., those who increased LNCSB intake vs. decreased or no change). The remaining articles included a continuous measure of LNCSB intake as the comparator.

#### Outcomes

In adults, outcomes included body composition and risk of obesity. The most commonly reported outcomes were waist circumference (15 articles), weight (14 articles), and BMI (10 articles). Fewer articles reported incidence of overweight or obesity, likelihood of achieving 5% weight loss, or measures of body composition other than waist circumference. Study personnel measured outcomes in all of the RCTs and over half (11 of 19) of the PCS articles; 8 PCS articles based outcomes on self-reported height, weight, and/or waist circumference.^^18,19,29,35,37,40–42^^

##### Body Composition Outcomes

All of the RCT articles reported body composition outcomes, with most including waist circumference data. One article included percent change in hip circumference.^^44^^ Maersk et al^^34^^ was the only RCT that included measures of visceral adipose tissue. Nine of the 19 PCS articles included body composition outcomes, including waist circumference, visceral adipose tissue, subcutaneous adipose tissue, and abdominal obesity.^^21,23–25,29–31,36,42^^

##### Risk of Obesity Outcomes

Seven RCT articles included outcomes related to risk of obesity, such as BMI, weight, and likelihood of achieving 5% weight loss.^^20,32,33,38,39,43,44^^ Sixteen PCS articles reported risk of obesity outcomes, including BMI, weight, overweight or obesity incidence, and weight loss.^^18,19,21,22,25–31,35,37,40–42^^

### Synthesis of the evidence

There was only one study conducted exclusively in older adults^25^ and most articles had a mean baseline age less than 60 years; therefore, evidence in adults and older adults was synthesized together. There were two instances in which 2 articles were published from the same randomized trial: Madjd, 2015,^^32^^ and Madjd, 2018,^^33^^ and Peters, 2014,^^38^^ and Peters, 2016.^^39^^ Madjd, 2015, and Peters, 2014, reported results from an intermediate timepoint of the intervention or post-trial follow-up period, and they were deprioritized in evidence synthesis in favor of the longer-term results from Madjd, 2018, and Peters, 2016. The evidence synthesis reflects this de-prioritization.

#### Randomized Controlled Trials

Overall, there were inconsistencies in the type of beverage and amount of LNCSB consumed in the RCT interventions. Relative to the comparator, 4 of the 6 prioritized RCT articles did not report favorable outcomes. Vazquez-Duran et al^^44^^ found that after 6 months, both the diet beverages and the no-sweetened beverages groups lowered their BMI, with smaller reductions in the diet beverages group compared with the no-sweetened beverages group. Similarly, Madjd et al^^33^^ reported reductions in weight and BMI in both the diet beverage and water control groups, with the diet beverages group losing less weight and having a smaller BMI reduction than the control group. Bonnet et al^^20^^ and Tate et al^^43^^ found no difference in weight between groups.

Two RCTs found a beneficial effect of LNCSB versus the comparator.^^39,43^^ In both studies, the intervention group had a higher likelihood of achieving 5% weight loss compared with the attention control or water groups, respectively. Peters et al^^39^^ also noted greater reduction in waist circumference after 1 year in the LNCSB intervention group. This was the only article reporting a beneficial effect of LNCSB on body composition measures compared with the control group; all others found no difference between groups^^20,33,43,44^^ or inferiority compared with the control group.^^44^^

#### Prospective Cohort Studies

Eleven of the 19 PCS articles reported statistically significant associations between LNCSB intake and body composition and/or risk of obesity outcomes. Since energy intake is an important covariate when interpreting studies on the relationship between LNCSB consumption and body composition and risk of obesity, articles were organized by whether or not they adjusted for total energy intake. Both approaches were considered within the evidence synthesis.

##### Body Composition Outcomes

Nine PCS articles reported body composition outcomes. Findings were mixed: 4 articles found an unfavorable association between LNCSB intake and measures of body composition,^^21,23–25^^ 4 articles reported neutral results,^^29,31^^(Konieczna, 2019}^36^ and 1 article found a beneficial relationship.^^42^^

Six articles adjusted for TEI, half of which noted unfavorable associations between LNCSB intake and waist circumference and/or abdominal obesity. Duffey et al^^23^^ categorized participants at baseline as LNCSB consumers or non-consumers; after 20 years of follow-up, there was a greater risk of high waist circumference in LNCSB consumers compared to non-consumers. In a Dutch cohort with over 78,000 participants, Buso et al^^21^^ found an association between LNCSB intake and higher waist circumference and abdominal obesity over a median 4 years of follow-up. Median intake was low (0.01 servings per day), but over half of participants reported consuming LNCSB. In a secondary analysis of data from the PREvención con Dieta MEDiterránea (PREDIMED) trial, higher intake of LNCSB was associated with greater risk of abdominal obesity.^^24^^ However, two cohorts with mean ages >60 years found no relationship between LNCSB and waist circumference over mean 5 year follow-up periods,^^30,36^^ and Ma et al^^31^^ found no relationship between LNCSB and change in visceral or subcutaneous adipose tissue over 6 years.

In articles that did not adjust for TEI, findings were split. Fowler et al^^25^^ found an association between daily diet soda consumption and greater change in waist circumference over a mean 9.4 years of follow-up; sub-group analyses found this unfavorable association to be significant specifically in men, those of European-American descent, and those with a BMI ≥30 kg/m^2^. In an all-female cohort of Mexican teachers, Stern et al^^42^^ found an association between increasing sugar-free soda intake and lower self-reported waist circumference; however, only 20% of the sample consumed sugar-free soda and mean baseline intake was 0.1 servings per week. In a cohort of Danish women, there was no association between LNCSB and waist circumference or visceral adipose tissue over 9 to 16 years of follow-up.^^29^^

##### Risk of Obesity Outcomes

Fifteen articles reported risk of obesity outcomes, including weight (10 articles),^^18,19,21,22,30,31,35,37,41,42^^ BMI (6 articles),^^25–29,40^^ and incidence of overweight and/or obesity (3 articles).^^21,26,29^^

Two articles from large U.S. cohorts with measurements of LNCSB intake every 4 years found significant associations between increasing LNCSB intake and lower body weight over 12 to 20 years of follow-up.^^35,37^^ Another article with data from the Nurses’ Health Study II found that participants who increased their intake of diet soft drinks over 4 years gained less weight compared with those that decreased their intake.^^41^^ However, this article did not adjust for TEI. Of note, these 3 articles included overlapping cohorts and all included self-reported weight. Four articles found no association between LNCSB and weight^^18,30,31,42^^; all but one^^42^^ of them adjusted for TEI in their analyses. Two articles reported unfavorable associations between LNCSB intake and body weight. Buso et al^^21^^ found a relationship between higher consumption of LNCSB and higher body weight after a median 4 years of follow-up. Bes-Rastrollo et al^^19^^ also found an association between higher LNCSB intake and higher self-reported weight change over 8 years of follow-up in the all-female Nurses’ Health Study II cohort; however, this association was only for caffeine-free LNCSB. There was no association with low-calorie cola overall. In a secondary analysis of an RCT of 810 adults enrolled in a behavioral intervention to lower blood pressure (95% with overweight or obesity), Chen et al^^22^^ found no association between weight loss at 18 months and LNCSB intake.

Among articles reporting BMI outcomes, 4 found unfavorable associations between LNCSB intake and BMI,^25–28^ while 2 found null associations.^^29,40^^ One study in a small cohort (n=466) reported a ~0.4 kg/m^2^ increment in BMI over 10 years for high consumers of LNCSB (≥1 soda/day) versus none/non-users.^^25^^ The second article reported higher BMI with LNCSB intake in both men and women; this study dichotomized participants by frequency of diet soft drink intake at baseline (<1 per month versus ≥1 per month) and reported on BMI 13 years later.^^28^^ Analyses from San Antonio Heart Study participants found a dose-response relationship between increasing category of LNCSB intake at baseline and greater change in BMI over 7–8 years of follow-up.^^26^^ Garduno-Alanis et al^^27^^ reported an association between LNCSB intake and BMI increase over 3 years; over 97% of participants in this cohort (total n=5,205) were never-LNCSB drinkers. Qi et al^^40^^ looked at LNCSB intake and BMI in three cohorts: the Nurses Health Study (NHS), Health Professionals Follow-Up Study (HPFS), and the Women’s Genome Health Study (WGHS). There was no association with BMI (based on self-reported height and weight) after 18 years (NHS), 12 years (HPFS), or 6 years (WGHS). Hinkle et al found no association with BMI over 9–16 years of follow-up in a cohort of Danish women with a history of gestational diabetes.^^29^^

Two articles found a relationship between higher LNCSB intake and higher risk of overweight and/or obesity. One of these was in a cohort of over 78,000 Dutch adults,^^21^^ which found a consistent relationship whether or not TEI was accounted for. Fowler et al demonstrated a dose-response relationship between LNCSB intake and both overweight/obesity and obesity incidence after 7–8 years among participants who had BMI <25 kg/m^2^ at baseline. Risk increased the most between non-use and the first quartile (<3 drinks per week) but continued rising toward a doubling of risk for the highest quartile (≥22 drinks per week). However, this study did not adjust for TEI. Similar to the BMI findings above, Hinkle et al found no association between LNCSB and obesity risk.^^29^^

### Conclusion statement and grade

The Committee developed and graded a conclusion statement for the systematic review question: “What is the relationship between low- and no-calorie sweetened beverage consumption and growth, body composition, and risk of obesity?” based on their review of evidence in adults. (see Table 6).

Table 6 Conclusion statement and grade for LNCSB and body composition and risk of obesity in adults and older adults

Conclusion Statement | Low- and no-calorie sweetened beverage consumption by adults and older adults, compared with water or lower amounts of low- and no-calorie sweetened beverages, is not associated with a change in body composition and risk of obesity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 8 RCTs, 19 prospective cohort studies
Consistency | Some concerns with variation in the direction of findings, primarily in observational studies
Precision | Some concerns with small sample sizes; variation in metrics across studies
Risk of bias | Substantial concerns, particularly due to confounding and missing data in observational studies
Directness | Some concerns with directness in observational studies
Generalizability | Substantial concerns with applicability to the U.S. population due to low diversity in reported race and/or ethnicity and socioeconomic position

#### Assessment of the evidence

The body of evidence underlying the conclusion statement includes 8 RCTs and 19 PCS. The evidence was graded based on an assessment of five grading elements, as described below. In addition, publication bias was also a consideration; however, it was not deemed a serious concern for this body of evidence because multiple studies reported only nonsignificant findings while others reported significant findings or a mix of significant and nonsignificant.

##### Consistency

Most RCTs and cohort studies reported an association between LNCSB intake and measures of body composition and/or risk of obesity. However, the direction of findings was inconsistent across the body of evidence and frequently even within the same study, if an article reported multiple outcomes. There were also inconsistencies in comparators in the RCTs, definitions of LNCSB among observational studies, and units used to assess intake.

##### Precision

The body of evidence demonstrates limited precision mostly due to small sample sizes. Samples sizes of the RCTs ranged from 12 to 145 participants per arm. Four PCS had sample sizes less than 2,000 participants. There was also imprecision in the categorical cutoffs used in the observational analyses; for example, one paper^^28^^ grouped all participants who consumed LNCSB at least once a month together, meaning that those who consumed LNCSB multiple times daily were in the same category as those who consumed them once per month.

##### Risk of bias

Risk of bias assessments for each article are detailed in Table 12 (RCTs) and Table 13 (PCS). There were substantial concerns with risk of bias, mainly due to confounding and missing data in the observational studies. Only two of the 19 PCS articles accounted for all key confounders; race and/or ethnicity and SEP were the confounders most commonly not reported. Selection of the reported results was a concern in both RCTs and observational studies, as most did not have a predefined data analysis plan.

##### Directness

There were some concerns with directness, given that many studies had broader objectives beyond assessing LNCSB and body composition and risk of obesity. Many studies also assessed multiple dietary exposures, including LNCSB.

##### Generalizability

Most studies were conducted in the United States. All but one RCT^^20^^ were in participants with overweight or obesity; observational studies included participants with a range of anthropometry at baseline (e.g., BMI, percent of study population with overweight or obesity). The most substantial concerns with generalizability were due to low diversity in reported race and/or ethnicity and socioeconomic position. Most articles that reported race and/or ethnicity data were conducted in predominantly white, non-Hispanic populations, and most articles that reported SEP data were conducted in middle- to higher-SEP populations. Nearly half of all articles did not report race and/or ethnicity data, and one-third did not report SEP data.

## Individuals during pregnancy and postpartum

### Description of the evidence

There was no eligible evidence in individuals during pregnancy. One article was included in individuals during postpartum. Evidence for consumption of LNCSB in postpartum and postpartum weight change is summarized in Table 14. The PCS in individuals during postpartum enrolled a multi-ethnic cohort (75% racial and/or ethnic minorities) of individuals aged 20 to 45 years and assessed postpartum weight retention at one year postpartum.^^45^^ Diet soda intake (with or without caffeine) was measured at baseline using a 13-item questionnaire and participants were categorically grouped by intake of diet soda: none, <1, or ≥2 servings per week. Postpartum weight retention was calculated by subtracting self-reported pre-pregnancy weight from measured weight at 1 year postpartum.

### Synthesis of the evidence

There were no studies on LNCSB consumption during pregnancy and gestational weight gain. The article on LNCSB intake and postpartum weight change found that LNCSB intake was not associated with postpartum weight retention after 1 year.^^45^^ The risk of bias assessment for this article is found in Table 15.

### Conclusion statements and grades

The Committee developed and graded conclusion statements for the systematic review question: “What is the relationship between low- and no-calorie sweetened beverage consumption and growth, body composition, and risk of obesity?” based on their review of evidence in individuals during pregnancy and postpartum (see Table 7 and Table 8). Conclusion statements could not be drawn for these populations due to a lack of evidence.

Table 7 Conclusion statement and grade for LNCSB and gestational weight gain

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened beverage consumption during pregnancy and adequacy of gestational weight gain because there is no evidence available.
Grade | Grade Not Assignable
Body of Evidence | 0 articles
Rationale | There were no eligible articles examining low- and no-calorie sweetened beverage consumption and gestational weight gain.

Table 8 Conclusion statement and grade for LNCSB and postpartum weight change

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened beverage consumption during postpartum and postpartum weight change because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 article
Rationale | There was only one eligible article examining low- and no-calorie sweetened beverage consumption and postpartum weight change; therefore, no conclusion could be drawn.