# Plain language summary

### What is the question?

The question is: What is the relationship between low- and no-calorie sweetened beverage consumption and growth, body composition, and risk of obesity? The populations of interest for this question include children, adolescents, adults, older adults, and individuals during pregnancy and postpartum.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025–2030. This review updated an existing review that was conducted by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

- Low- and no-calorie sweetened beverage consumption by children and adolescents may not be associated with growth, body composition, and risk of obesity. This conclusion statement is based on evidence graded as limited.
- Low- and no-calorie sweetened beverage consumption by adults and older adults, compared with water or lower amounts of low- and no-calorie sweetened beverages, is not associated with a change in body composition and risk of obesity. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened beverage consumption during pregnancy and adequacy of gestational weight gain because there is no evidence available.
- A conclusion statement cannot be drawn about the relationship between low- and no-calorie sweetened beverage consumption during postpartum and postpartum weight change because there is not enough evidence available.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and May 2023.