# Appendix 5 Excluded articles

The existing systematic review for this question included 152 articles. However, after applying the inclusion and exclusion criteria established for the update to that review, seven articles were no longer eligible for inclusion. The following articles were excluded from the existing systematic review due to updated eligibility criteria:

1. Faghih S, Abadi AR, Hedayati M, Kimiagar SM. Comparison of the effects of cows' milk, fortified soy milk, and calcium supplement on weight and fat loss in premenopausal overweight and obese women. Nutr Metab Cardiovasc Dis. 2011;21(7):499–503. doi: 10.1016/j.numecd.2009.11.013. (Study duration)20227261
2. Fathi Y, Faghih S, Zibaeenezhad MJ, Tabatabaei SH. Kefir drink leads to a similar weight loss, compared with milk, in a dairy-rich non-energy-restricted diet in overweight or obese premenopausal women: a randomized controlled trial. Eur J Nutr. 2016;55(1):295–304. doi: 10.1007/s00394-015-0846-9. (Study duration)25648739
3. Fresan U, Gea A, Bes-Rastrollo M, Ruiz-Canela M, Martinez-Gonzalez MA. Substitution models of water for other beverages, and the incidence of obesity and weight gain in the SUN cohort. Nutrients. 2016;8(11). doi: 10.3390/nu8110688. (Intervention/exposure)
4. Houchins JA, Burgess JR, Campbell WW, Beverage vs. solid fruits and vegetables: effects on energy intake and body weight. Obesity. 2012;20(9):1844–1850. doi: 10.1038/oby.2011.192. (Study duration)21720441
5. Lee YJ, Seo JA, Yoon T, Effects of low-fat milk consumption on metabolic and atherogenic biomarkers in Korean adults with the metabolic syndrome: a randomised controlled trial. J Hum Nutr Diet. 2016;29(4):477–486. doi: 10.1111/jhn.12349. (Study duration)26945812
6. Pourahmadi Z, Mahboob S, Saedisomeolia A, Reykandeh MT. The effect of tomato juice consumption on antioxidant status in overweight and obese females. Women Health. 2015;55(7):795–804. doi: 10.1080/03630242.2015.1050546. (Study duration)26086066
7. Simao TN, Lozovoy MA, Simao AN, Reduced-energy cranberry juice increases folic acid and adiponectin and reduces homocysteine and oxidative stress in patients with the metabolic syndrome. Br J Nutr. 2013;110(10):1885–1894. doi: 10.1017/s0007114513001207. (Study duration)23750500

The following table lists the articles excluded after full-text screening for the updated systematic review literature search (Appendix 4). At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 13 Articles excluded after full-text screening

| Citation | Rationale
1 | [No authors listed]. Can drinking milk really help me lose weight?. Mayo Clin Womens Healthsource. 2006. 10:10. | Publication status
2 | [No authors listed]. Milk as an essential factor in pregnancy. Reproductive biomedicine online. 2006. 12:736.16792850 | Pub status
3 | [No authors listed]. Trying to lose weight? Watch what you drink. Mayo Clin Womens Healthsource. 2008. 12:7. | Publication status
4 | Abdalgwad, R, Rafey, MF, Foy, S, Newell, M, Davenport, C, O'Keeffe, DT, Finucane, FM. Long-Term Changes in Weight in Patients With Severe and Complicated Obesity After Completion of a Milk-Based Meal Replacement Programme. Front Nutr. 2020. 7:551068. doi:10.3389/fnut.2020.551068.33117840 | Int/Exp: Not relevant
5 | Abedini, M, Ghasemi-Tehrani, H, Tarrahi, MJ, Amani, R. The effect of concentrated pomegranate juice consumption on risk factors of cardiovascular diseases in women with polycystic ovary syndrome: A randomized controlled trial. Phytother Res. 2021. 35:442–451. doi:10.1002/ptr.6820.32767710 | EXCLUDE - All other health status criteria
6 | Adegboye, ARA, Santana, DD, Dos Santos, PPT, Cocate, PG, Benaim, C, de Castro, MBT, Schlüssel, MM, Kac, G, Heitmann, BL. Exploratory efficacy of calcium-vitamin D milk fortification and periodontal therapy on maternal oral health and metabolic and inflammatory profile. Nutrients. 2021. 13:1–15. doi:10.3390/nu13030783. | Int/Exp: Not relevant; Outcome
7 | Aggazzotti, G, Righi, E, Fantuzzi, G, Biasotti, B, Ravera, G, Kanitz, S, Barbone, F, Sansebastiano, G, Battaglia, MA, Leoni, V, Fabiani, L, Triassi, M, Sciacca, S. Chlorination by-products (CBPs) in drinking water and adverse pregnancy outcomes in Italy. J Water Health. 2004. 2:233–47.15666965 | Study design; Outcome; Population
8 | Aguilar, SS, Wengreen, HJ, Dew, J. Skin Carotenoid Response to a High-Carotenoid Juice in Children: A Randomized Clinical Trial. J Acad Nutr Diet. 2015. 115:1771–8. doi:10.1016/j.jand.2015.06.011 26254845 | Comparator; Outcome
9 | Alexy, U, Kersting, M. Time trends in the consumption of dairy foods in German children and adolescents. Eur J Clin Nutr. 2003. 57:1331–7. doi:10.1038/sj.ejcn.1601696 14506497 | Outcome
10 | Alfonso Mayén, V, Ogunlusi, A, Wright, CM, Garcia, AL. Childhood stunting and micronutrient status unaffected by RCT of micronutrient fortified drink. Matern Child Nutr. 2022;18(1):e13256. doi:10.1111/mcn.13256.34355514 | Country
11 | Ali, MA, Strandvik, B, Palme-Kilander, C, Yngve, A. Lower polyamine levels in breast milk of obese mothers compared to mothers with normal body weight. J Hum Nutr Diet. 2013. 26 Suppl 1:164–70. doi:10.1111/jhn.12097 23627874 | Intervention/Exposure; Outcome
12 | Alikhani, S, Etemad, Z, Azizbeigi, K. Effects of spinning workout and green tea consumption on the anti-inflammatory and inflammatory markers and body composition of overweight women. Journal of Kermanshah University of Medical Sciences. 2021. 25:n.pag. doi:10.5812/jkums.110116. | Int/Exp: Not relevant
13 | Allman-Farinelli, M, Partridge, SR, McGeechan, K, Balestracci, K, Hebden, L, Wong, A, Phongsavan, P, Denney-Wilson, E, Harris, MF, Bauman, A. A Mobile Health Lifestyle Program for Prevention of Weight Gain in Young Adults (TXT2BFiT): nine-Month Outcomes of a Randomized Controlled Trial. JMIR mhealth and uhealth. 2016. 4:e78. doi:10.2196/mhealth.5768.27335237 | Int/Exp: Not relevant
14 | Almberg, KS, Turyk, ME, Jones, RM, Rankin, K, Freels, S, Stayner, LT. Atrazine Contamination of Drinking Water and Adverse Birth Outcomes in Community Water Systems with Elevated Atrazine in Ohio, 2006(-)2008. Int J Environ Res Public Health. 2018. 15(9):1889. doi:10.3390/ijerph15091889 30200320 | Study design; Intervention/Exposure; Outcome
15 | Alperet, DJ, Rebello, SA, Khoo, EY, Tay, Z, Seah, SS, Tai, BC, Tai, ES, Emady-Azar, S, Chou, CJ, Darimont, C, van Dam, RM. The effect of coffee consumption on insulin sensitivity and other biological risk factors for type 2 diabetes: a randomized placebo-controlled trial. Am J Clin Nutr. 2020. 111:448–458. doi:10.1093/ajcn/nqz306.31891374 | Comparator
16 | Alustiza, E, Perales, A, Mateo-Abad, M, Ozcoidi, I, Aizpuru, G, Albaina, O, Vergara, I. Tackling risk factors for type 2 diabetes in adolescents: PRE-STARt study in Euskadi. An Pediatr (Engl Ed). 2021. 95:186–196. doi:10.1016/j.anpede.2020.11.005.34384737 | Int/Exp: Not relevant
17 | Alves-Santos, NH, Cocate, PG, Eshriqui, I, Benaim, C, Barros, EG, Emmett, PM, Kac, G. Dietary patterns and their association with adiponectin and leptin concentrations throughout pregnancy: a prospective cohort. Br J Nutr. 2018. 119:320–329. doi:10.1017/s0007114517003580 29345609 | Intervention/Exposure
18 | Amagase, H, Sun, B, Nance, DM. Immunomodulatory effects of a standardized Lycium barbarum fruit juice in Chinese older healthy human subjects. J Med Food. 2009. 12:1159–65. doi:10.1089/jmf.2008.0300 19857084 | Intervention/exposure; EXCLUDE; Country
19 | Andersson, C, Sullivan, L, Benjamin, EJ, Aragam, J, Jacques, P, Cheng, S, Vasan, RS. Association of soda consumption with subclinical cardiac remodeling in the Framingham heart study. Metabolism. 2015. 64:208–12. doi:10.1016/j.metabol.2014.10.009 25456096 | Study design; Outcome
20 | Angelopoulos, TJ, Lowndes, J, Sinnett, S, Rippe, JM. Fructose containing sugars do not raise blood pressure or uric acid at normal levels of human consumption. J Clin Hypertens (Greenwich). 2015. 17:87–94. doi:10.1111/jch.12457 25496265 | Intervention/exposure; Comparator
21 | Anleu, E, Reyes, M, Araya, BM, Flores, M, Uauy, R, Garmendia, ML. Effectiveness of an Intervention of Dietary Counseling for Overweight and Obese Pregnant Women in the Consumption of Sugars and Energy. Nutrients. 2019. 11(2):385. doi:10.3390/nu11020385 30781781 | Intervention/Exposure; Outcome
22 | Antonakou, A, Papoutsis, D, Panou, I, Chiou, A, Matalas, AL. Role of exclusive breastfeeding in energy balance and weight loss during the first six months postpartum. Clin Exp Obstet Gynecol. 2013. 40:485–8.24597239 | Intervention/Exposure
23 | Antonakou, A, Skenderi, KP, Chiou, A, Anastasiou, CA, Bakoula, C, Matalas, AL. Breast milk fat concentration and fatty acid pattern during the first six months in exclusively breastfeeding Greek women. Eur J Nutr. 2013. 52:963–73. doi:10.1007/s00394–012-0403–8 22752261 | Intervention/Exposure; Outcome
24 | Arthur, R, Kirsh, VA, Rohan, TE. Associations of coffee, tea and caffeine intake with risk of breast, endometrial and ovarian cancer among Canadian women. Cancer Epidemiol. 2018. 56:75–82. doi:10.1016/j.canep.2018.07.013 30075330 | Outcome
25 | Arvizu, M, Stuart, J, Rich-Edwards, J, Gaskins, A, Rosner, B, Chavarro, J. Adherence to Pre-pregnancy DASH Dietary Pattern and Diet Recommendations from the American Heart Association and the Risk of Preeclampsia (OR35–06-19). Curr Dev Nutr. 2019. 3:Supp1. doi:10.1093/cdn/nzz048.OR35–06-19 | Pub status
26 | Assaf-Balut, C, de la Torre, NG, Fuentes, M, Durán, A, Bordiú, E, Del Valle, L, Valerio, J, Jiménez, I, Herraiz, MA, Izquierdo, N, Torrejón, MJ, de Miguel, MP, Barabash, A, Cuesta, M, Rubio, MA, Calle-Pascual, AL. A high adherence to six food targets of the mediterranean diet in the late first trimester is associated with a reduction in the risk of materno-foetal outcomes: The st. carlos gestational diabetes mellitus prevention study. Nutrients. 2019. 11(1):66. doi:10.3390/nu11010066 | Intervention/Exposure; Outcome
27 | Atalla, M, Pinto, AJ, Mielke, GI, Benatti, FB, Gualano, B. Impact of a Real-World Lifestyle Intervention in an Entire Latin American City with More Than 50,000 People. Obesity (Silver Spring). 2019. 27:1967–1974. doi:10.1002/oby.22575.31657154 | Study design; Int/Exp: Not relevant
28 | Aumueller, N, Gruszfeld, D, Gradowska, K, Escribano, J, Ferré, N, Rousseaux, D, Hoyos, J, Verduci, E, ReDionigi, A, Koletzko, B, Grote, V. Associations of sugar intake with anthropometrics in children from ages 2 until 8 years in the EU Childhood Obesity Project. European Journal of Nutrition. 2020. 59:2593–2601. doi:10.1007/s00394–019-02107–0.31642983 | Int/Exp: Not relevant
29 | Azad, MB, Sharma, AK, de Souza, RJ, Dolinsky, VW, Becker, AB, Mandhane, PJ, Turvey, SE, Subbarao, P, Lefebvre, DL, Sears, MR. Association Between Artificially Sweetened Beverage Consumption During Pregnancy and Infant Body Mass Index. JAMA Pediatr. 2016. 170:662–70. doi:10.1001/jamapediatrics.2016.0301 27159792 | Outcome; Population
30 | Babio, N, Becerra-Tomás, N, Martínez-González, MÁ, Corella, D, Estruch, R, Ros, E, Sayón-Orea, C, Fitó, M, Serra-Majem, L, Arós, F, Lamuela-Raventós, RM, Lapetra, J, Gómez-Gracia, E, Fiol, M, Díaz-López, A, Sorlí, JV, Martínez, JA, Salas-Salvadó, J. Consumption of Yogurt, Low-Fat Milk, and Other Low-Fat Dairy Products Is Associated with Lower Risk of Metabolic Syndrome Incidence in an Elderly Mediterranean Population. J Nutr. 2015. 145:2308–16. doi:10.3945/jn.115.214593 26290009 | Duplicate; Other; Included in 2020 DGs
31 | Badillo, P, Salgado, P, Bravo, P, Guevara, K, Acurio, J, Gonzalez, MA, Oyarzun, C, San Martin, R, Escudero, C. High plasma adenosine levels in overweight/obese pregnant women. Purinergic Signal. 2017. 13:479–488. doi:10.1007/s11302–017-9574–3 28721552 | Study design; Intervention/Exposure
32 | Baião Ddos, S, Conte-Junior, CA, Paschoalin, VM, Alvares, TS. Beetroot juice increase nitric oxide metabolites in both men and women regardless of body mass. Int J Food Sci Nutr. 2016. 67:40–6. doi:10.3109/09637486.2015.1121469 26653541 | Intervention/exposure; Outcome
33 | Bakker, R, Steegers, EA, Obradov, A, Raat, H, Hofman, A, Jaddoe, VW. Maternal caffeine intake from coffee and tea, fetal growth, and the risks of adverse birth outcomes: the Generation R Study. Am J Clin Nutr. 2010. 91:1691–8. doi:10.3945/ajcn.2009.28792 20427730 | Outcome; Population
34 | Bakuradze, T, Lang, R, Hofmann, T, Eisenbrand, G, Schipp, D, Galan, J, Richling, E. Consumption of a dark roast coffee decreases the level of spontaneous DNA strand breaks: a randomized controlled trial. Eur J Nutr. 2015. 54:149–56. doi:10.1007/s00394–014-0696-x 24740588 | Outcome; EXCLUDE
35 | Balsan, G, Pellanda, LC, Sausen, G, Galarraga, T, Zaffari, D, Pontin, B, Portal, VL. Effect of yerba mate and green tea on paraoxonase and leptin levels in patients affected by overweight or obesity and dyslipidemia: A randomized clinical trial. Nutrition Journal. 2019. 18(1):5. doi:10.1186/s12937–018-0426-y.30660196 | Outcome
36 | Baltaci A, Hurtado Choque GA, Davey C, Reyes Peralta A, Alvarez de Davila S, Zhang Y, Gold A, Larson N, Reicks M. Padres Preparados, Jóvenes Saludables: intervention impact of a randomized controlled trial on Latino father and adolescent energy balance-related behaviors. BMC Public Health. 2022. 22(1):1932. doi:10.1186/s12889–022-14284–5.36258168 | Int/Exp: Not relevant
37 | Barr, SI, McCarron, DA, Heaney, RP, Dawson-Hughes, B, Berga, SL, Stern, JS, Oparil, S. Effects of increased consumption of fluid milk on energy and nutrient intake, body weight, and cardiovascular risk factors in healthy older adults. J Am Diet Assoc. 2000. 100:810–7. doi:10.1016/s0002–8223(00)00236–4 10916520 | Duplicate; Other; Included in 2020 DGs
38 | Bartakova, V, Kuricova, K, Zlamal, F, Belobradkova, J, Kankova, K. Differences in food intake and genetic variability in taste receptors between Czech pregnant women with and without gestational diabetes mellitus. Eur J Nutr. 2018. 57:513–521. doi:10.1007/s00394–016-1334–6 27757593 | Intervention/Exposure; Outcome
39 | Bartok, CJ, Ventura, AK. Mechanisms underlying the association between breastfeeding and obesity. International Journal of Pediatric Obesity. 2009. 4:196–204. doi:10.3109/17477160902763309 19922033 | Study design
40 | Basu, A, Betts, NM, Ortiz, J, Simmons, B, Wu, M, Lyons, TJ. Low-energy cranberry juice decreases lipid oxidation and increases plasma antioxidant capacity in women with metabolic syndrome. Nutr Res. 2011. 31:190–6. doi:10.1016/j.nutres.2011.02.003 21481712 | Intervention/exposure; Comparator
41 | Beardsall, A, Perreault, M, Farncombe, T, Vanniyasingam, T, Thabane, L, Teo, KK, Atkinson, SA. Maternal and child factors associated with bone length traits in children at 3years of age. Bone. 2019. 127:1–8. doi:10.1016/j.bone.2019.05.025 31132508 | Outcome
42 | Beaudry, KM, Ludwa, IA, Thomas, AM, Ward, WE, Falk, B, Josse, AR. First-year university is associated with greater body weight, body composition and adverse dietary changes in males than females. PLoS One. 2019. 14:e0218554. doi:10.1371/journal.pone.0218554.31269047 | Int/exp: Not included bev type
43 | Beaudry, KM, Ludwa, IA, Thomas, AM, Ward, WE, Falk, B, Josse, AR. First-year university is associated with greater body weight, body composition and adverse dietary changes in males than females. PLoS One. 2019. 14:e0218554. doi:10.1371/journal.pone.0218554.31269047 | Int/Exp: Not relevant
44 | Bech, BH, Frydenberg, M, Henriksen, TB, Obel, C, Olsen, J. Coffee Consumption During Pregnancy and Birth Weight: Does Smoking Modify the Association?. Journal of Caffeine Research. 2015. 5:65–72. doi:10.1089/jcr.2015.0001 | Outcome; Population
45 | Bech, BH, Obel, C, Henriksen, TB, Olsen, J. Effect of reducing caffeine intake on birth weight and length of gestation: randomised controlled trial. Bmj. 2007. 334:409. doi:10.1136/bmj.39062.520648.BE 17259189 | Outcome
46 | Bellikci-Koyu E, Sarer-Yurekli BP, Karagozlu C, Aydin-Kose F, Ozgen AG, Buyuktuncer Z. Probiotic kefir consumption improves serum apolipoprotein A1 levels in metabolic syndrome patients: a randomized controlled clinical trial. Nutr Res. 2022;102:59–70. doi:10.1016/j.nutres.2022.02.006 35405603 | Comparator
47 | Bellikci-Koyu, E, Sarer-Yurekli, BP, Akyon, Y, Aydin-Kose, F, Karagozlu, C, Ozgen, AG, Brinkmann, A, Nitsche, A, Ergunay, K, Yilmaz, E, Buyuktuncer, Z. Effects of Regular Kefir Consumption on Gut Microbiota in Patients with Metabolic Syndrome: A Parallel-Group, Randomized, Controlled Study. Nutrients. 2019. 11(9):2089. doi:10.3390/nu11092089.31487797 | Int/exp: Not included bev type; Comparator
48 | Bellikci-Koyu, E, Sarer-Yurekli, BP, Akyon, Y, Aydin-Kose, F, Karagozlu, C, Ozgen, AG, Brinkmann, A, Nitsche, A, Ergunay, K, Yilmaz, E, Buyuktuncer, Z. Effects of Regular Kefir Consumption on Gut Microbiota in Patients with Metabolic Syndrome: A Parallel-Group, Randomized, Controlled Study. Nutrients. 2019. 11(9):2089. doi:10.3390/nu11092089 31487797 | Intervention/exposure; Comparator
49 | Berkey, CS, Willett, WC, Tamimi, RM, Rosner, B, Frazier, AL, Colditz, GA. Dairy intakes in older girls and risk of benign breast disease in young women. Cancer Epidemiol Biomarkers Prev. 2013. 22:670–4. doi:10.1158/1055–9965.Epi-12–1133 23542805 | Outcome
50 | Bes-Rastrollo, M, van Dam, RM, Martinez-Gonzalez, MA, Li, TY, Sampson, LL, Hu, FB. Prospective study of dietary energy density and weight gain in women. Am J Clin Nutr. 2008. 88:769–77. doi:10.1093/ajcn/88.3.769 18779295 | Duplicate; Other; Included in 2020 DGs
51 | Bhatia, S, Saraswat, S. Effect of Japan water therapy infused with cinnamon on body weight, waist/hip ratio, and body mass index of overweight and obese subjects. Asian Journal of Pharmaceutical and Clinical Research. 2019. 12:302–305. doi:10.22159/ajpcr.2019.v12i9.34269. | Int/Exp: Not relevant; Comparator
52 | Bonjour, JP, Chevalley, T, Ammann, P, Slosman, D, Rizzoli, R. Gain in bone mineral mass in prepubertal girls 3.5 years after discontinuation of calcium supplementation: a follow-up study. Lancet. 2001. 358:1208–12. doi:10.1016/s0140–6736(01)06342–5 11675056 | Intervention/exposure
53 | Borazjani F, Angali KA, Kulkarni SS. Milk and protein intake by pregnant women affects growth of foetus. J Health Popul Nutr. 2013;31(4):435–445. doi:10.3329/jhpn.v31i4.19991 24592584 | Outcome; Population
54 | Borgen, I, Aamodt, G, Harsem, N, Haugen, M, Meltzer, HM, Brantsæter, AL. Maternal sugar consumption and risk of preeclampsia in nulliparous Norwegian women. European Journal of Clinical Nutrition. 2012. 66:920–925. doi:10.1038/ejcn.2012.61 22713766 | Outcome
55 | Botton, J, Kogevinas, M, Gracia-Lavedan, E, Patelarou, E, Roumeliotaki, T, Iniguez, C, Santa Marina, L, Ibarluzea, J, Ballester, F, Mendez, MA, Chatzi, L, Sunyer, J, Villanueva, CM. Postnatal weight growth and trihalomethane exposure during pregnancy. Environ Res. 2015. 136:280–8. doi:10.1016/j.envres.2014.09.035 25460647 | Population
56 | Bracken, MB, Triche, EW, Belanger, K, Hellenbrand, K, Leaderer, BP. Association of maternal caffeine consumption with decrements in fetal growth. Am J Epidemiol. 2003. 157:456–66. doi:10.1093/aje/kwf220 12615610 | Outcome; Population
57 | Bracken, MB, Triche, EW, Belanger, K, Hellenbrand, K, Leaderer, BP. Association of maternal caffeine consumption with decrements in fetal growth. Am J Epidemiol. 2003. 157:456–66. doi:10.1093/aje/kwf220 12615610 | Intervention/exposure; Outcome
58 | Brembeck, P, Winkvist, A, Ohlsson, C, Lorentzon, M, Augustin, H. Determinants of microstructural, dimensional and bone mineral changes postpartum in Swedish women. Br J Nutr. 2016. doi:10.1017/s0007114516003998 | Intervention/Exposure; Outcome
59 | Broccoli S, Bonvicini L, Djuric O, Understanding the association between mother's education level and effectiveness of a child obesity prevention intervention: a secondary analysis of an RCT [published correction appears in Epidemiol Prev. 2021 May-Jun;45(3):131. doi: 10.19191/EP21.3.P131.071]34212704 | Intervention/Exposure
60 | Buntuchai, G, Pavadhgul, P, Kittipichai, W, Satheannoppakao, W. Traditional Galactagogue Foods and Their Connection to Human Milk Volume in Thai Breastfeeding Mothers. J Hum Lact. 2017. 33:552–559. doi:10.1177/0890334417709432 28609178 | Outcome
61 | Buscemi S, Corleo D, Buscemi C, Influence of Habitual Dairy Food Intake on LDL Cholesterol in a Population-Based Cohort. Nutrients. 2021;13(2):593. Published 2021 Feb 11. doi:10.3390/nu13020593 33670170 | Study design; Outcome
62 | Bzikowska-Jura, A, Czerwonogrodzka-Senczyna, A, Oledzka, G, Szostak-Wegierek, D, Weker, H, Wesolowska, A. Maternal Nutrition and Body Composition During Breastfeeding: Association with Human Milk Composition. Nutrients. 2018. 10(10): 1379. doi:10.3390/nu10101379 30262786 | Intervention/Exposure; Outcome
63 | Caire-Juvera, G, Casanueva, E, Bolanos-Villar, AV, de Regil, LM, Calderon de la Barca, AM. No changes in weight and body fat in lactating adolescent and adult women from Mexico. Am J Hum Biol. 2012. 24:425–31. doi: 10.1002/ajhb.22234 22344621 | Intervention/Exposure
64 | Campbell AP. Time for tea?. Diabetes SelfManag. 2004;21(2):8–12. | Study design
65 | Cao, WC, Zeng, Q, Luo, Y, Chen, HX, Miao, DY, Li, L, Cheng, YH, Li, M, Wang, F, You, L, Wang, YX, Yang, P, Lu, WQ. Blood Biomarkers of Late Pregnancy Exposure to Trihalomethanes in Drinking Water and Fetal Growth Measures and Gestational Age in a Chinese Cohort. Environ Health Perspect. 2016. 124:536–41. doi:10.1289/ehp.1409234 26340795 | Outcome; Population
66 | Capel, F, Bongard, V, Malpuech-Brugere, C, Karoly, E, Michelotti, GA, Rigaudiere, JP, Jouve, C, Ferrieres, J, Marmonier, C, Sebedio, JL. Metabolomics reveals plausible interactive effects between dairy product consumption and metabolic syndrome in humans. Clinical Nutrition. 2020. 39:1497–1509. doi:10.1016/j.clnu.2019.06.013.31279616 | Int/Exp: Not relevant; Outcome
67 | Cardoso, GA, Salgado, JM, Cesar, MDC, Donado-Pestana, CM. The Effects of Green Tea Consumption and Resistance Training on Body Composition and Resting Metabolic Rate in Overweight or Obese Women. Journal of medicinal food. 2013. 16:120–127. doi:10.1089/jmf.2012.0062.23140132 | Int/Exp: Not relevant
68 | Carwile, JL, Willett, WC, Wang, M, Rich-Edwards, J, Frazier, AL, Michels, KB. Milk Consumption after Age 9 Years Does Not Predict Age at Menarche. J Nutr. 2015. 145:1900–8. doi:10.3945/jn.115.214270 26136590 | Outcome
69 | Chan, GM, McElligott, K, McNaught, T, Gill, G. Effects of dietary calcium intervention on adolescent mothers and newborns: A randomized controlled trial. Obstet Gynecol. 2006. 108:565–71. doi: 10.1097/01.AQG.0000231721.42823.9e 16946216 | Outcome
70 | Chan, GM, McElligott, K, McNaught, T, Gill, G. Effects of dietary calcium intervention on adolescent mothers and newborns: A randomized controlled trial. Obstet Gynecol. 2006. 108:565–71. doi: 10.1097/01.AQG.0000231721,42823.9e 16946216 | Intervention/exposure
71 | Chee, WS, Suriah, AR, Chan, SP, Zaitun, Y, Chan, YM. The effect of milk supplementation on bone mineral density in postmenopausal Chinese women in Malaysia. Osteoporos Int. 2003. 14:828–34. doi:10.1007/s00198–003-1448–6 12915959 | Duplicate; Other; Included in 2020 DGs
72 | Chen, JL, Guedes, CM, Lung, AE. Smartphone-based Healthy Weight Management Intervention for Chinese American Adolescents: Short-term Efficacy and Factors Associated With Decreased Weight. Journal of Adolescent Health. 2019. 64:443–449. doi:10.1016/j.jadohealth.2018.08.022. | Duplicate
73 | Chen, L, Hu, FB, Yeung, E, Willett, W, Zhang, C. Prospective study of pre-gravid sugar-sweetened beverage consumption and the risk of gestational diabetes mellitus. Diabetes Care. 2009. 32:2236–41. doi:10.2337/dc09–0866 19940226 | Outcome
74 | Chen, Lei, Bell, Erin, Browne, Marilyn, Druschel, Charlotte, Romitti, Paul. Exploring Maternal Patterns of Dietary Caffeine Consumption Before Conception and During Pregnancy. Maternal & Child Health Journal. 2014. 18:2446–2455. doi:10.1007/s10995–014-1483–2 24791972 | Outcome
75 | Chen, LW, Fitzgerald, R, Murrin, CM, Mehegan, J, Kelleher, CC, Phillips, CM. Associations of maternal caffeine intake with birth outcomes: Results from the Lifeways Cross Generation Cohort Study. American Journal of Clinical Nutrition. 2018. 108:1301–1308. doi:10.1093/ajcn/nqy219 30339199 | Outcome; Population
76 | Chen, LW, Murrin, CM, Mehegan, J, Kelleher, CC, Phillips, CM. Maternal, but not paternal or grandparental, caffeine intake is associated with childhood obesity and adiposity: The Lifeways Cross-Generation Cohort Study. Am J Clin Nutr. 2019. 109:1648–1655. doi:10.1093/ajcn/nqz019 31136661 | Outcome
77 | Chew, B, Mathison, B, Kimble, L, McKay, D, Kaspar, K, Khoo, C, Chen, CYO, Blumberg, J. Chronic consumption of a low calorie, high polyphenol cranberry beverage attenuates inflammation and improves glucoregulation and HDL cholesterol in healthy overweight humans: a randomized controlled trial. European Journal of Nutrition. 2019. 58:1223–1235. doi:10.1007/s00394–018-1643-z.29476238 | Comparator; Outcome
78 | Chiang, KM, Pan, WH. Causal link between milk consumption and obesity? A 10-year longitudinal study and a mendelian randomization study. Food and Nutrition Research. 2021. 65:6300. doi:10.29219/FNR.V65.6300. | Country
79 | Chiochetta, M, Ferreira, EJ, Moreira, Itds, Avila, RCS, Oliveira, AA, Busnello, FM, Braganhol, E, Barschak, AG. Green Juice in Human Metabolism: A Randomized Trial. J Am Coll Nutr. Published online April 27, 2018. doi:10.1080/07315724.2018.1457458 | Intervention/exposure; Comparator
80 | Chiu, HF, Lin, TY, Shen, YC, Venkatakrishnan, K, Wang, CK. Improvement of green tea polyphenol with milk on skin with respect to antioxidation in healthy adults: a double-blind placebo-controlled randomized crossover clinical trial. Food Funct. 2016. 7:893–901. doi:10.1039/c5fo01271f 26686527 | Intervention/exposure
81 | Chiu, YH, Rifas-Shiman, SL, Kleinman, K, Oken, E, Young, JG. Effects of intergenerational exposure interventions on adolescent outcomes: An application of inverse probability weighting to longitudinal pre-birth cohort data. Paediatr Perinat Epidemiol. 2020. 34:366–375. doi:10.1111/ppe.12646.32162715 | Study design
82 | Chortatos, A, Haugen, M, Iversen, PO, Vikanes, A, Magnus, P, Veierod, MB. Nausea and vomiting in pregnancy: associations with maternal gestational diet and lifestyle factors in the Norwegian Mother and Child Cohort Study. Bjog. 2013. 120:1642–53. doi:10.1111/1471–0528.12406 23962347 | Intervention/Exposure; Outcome
83 | Chrysohoou, C, Panagiotakos, DB, Pitsavos, C, Zeimbekis, A, Zampelas, A, Papademetriou, L, Masoura, C, Stefanadis, C. The associations between smoking, physical activity, dietary habits and plasma homocysteine levels in cardiovascular disease-free people: the 'ATTICA' study. Vasc Med. 2004. 9:117–23. doi:10.1191/1358863x04vm542oa 15521701 | Study design
84 | Cleghorn, DB, OĽoughlin, PD, Schroeder, BJ, Nordin, BE. An open, crossover trial of calcium-fortified milk in prevention of early postmenopausal bone loss. Med J Aust. 2001. 175:242–5. doi:10.5694/j.1326–5377.2001.tb143554.x 11587253 | Intervention/exposure
85 | Coelho Nde, L, Cunha, DB, Esteves, AP, Lacerda, EM, Theme Filha, MM. Dietary patterns in pregnancy and birth weight. Rev Saude Publica. 2015. 49:62. doi:10.1590/s0034–8910.2015049005403 26398873 | Intervention/Exposure; Outcome
86 | Coelho Nde, L, Cunha, DB, Esteves, AP, Lacerda, EM, Theme Filha, MM. Dietary patterns in pregnancy and birth weight. Rev Saude Publica. 2015. 49:62. doi:10.1590/s0034–8910.2015049005403 26398873 | Intervention/exposure
87 | Cohen CC, Dabelea D, Michelotti G, Tang L, Shankar K, Goran MI, Perng W. Metabolome Alterations Linking Sugar-Sweetened Beverage Intake with Dyslipidemia in Youth: The Exploring Perinatal Outcomes among CHildren (EPOCH) Study.. Metabolites. 2022. 12(6):559. doi:10.3390/metabo12060559.35736491 | Outcome
88 | Colleran, HL, Lovelady, CA. Use of MyPyramid Menu Planner for Moms in a weight-loss intervention during lactation. J Acad Nutr Diet. 2012. 112:553–8. doi:10.1016/j.jand.2011.12.004 22709705 | Intervention/Exposure
89 | Costa CDS, Buffarini R, Flores TR, Neri D, Freitas Silveira M, Monteiro CA. Consumption of ultra-processed foods and growth outcomes in early childhood: 2015 Pelotas Birth Cohort. Br J Nutr. doi:10.1017/S0007114522002926. | Int/Exp: Not relevant
90 | Costa, Caroline dos Santos, Buffarini, Romina, Flores, Thaynã Ramos, Neri, Daniela, Freitas Silveira, Mariângela, Monteiro, Carlos Augusto. Consumption of ultra-processed foods and growth outcomes in early childhood: 2015 Pelotas Birth Cohort. British Journal of Nutrition. 2023. 129:2153–2160. doi:10.1017/S0007114522002926.36093936 | Int/Exp: Not relevant
91 | Costa, D, Warkentin, S, Oliveira, A. The effect of sugar-sweetened beverages at 4 years of age on appetitive behaviours of 7-year-olds from the Generation XXI birth cohort. British Journal of Nutrition. 2021. 126:790–800. doi:10.1017/S000711452000447X.33161915 | Outcome; Publication status
92 | Cranney, L, O'Hara, B, Gale, J, Rissel, C, Bauman, A, Phongsavan, P. Telephone based coaching for adults at risk of diabetes: impact of Australia's Get Healthy Service. Transl Behav Med. 2019. 9:1178–1185. doi:10.1093/tbm/ibz007.30753699 | Study design; Int/Exp: Not relevant
93 | Crézé, C, Notter-Bielser, ML, Knebel, JF, Campos, V, Tappy, L, Murray, M, Toepel, U. The impact of replacing sugar- by artificially-sweetened beverages on brain and behavioral responses to food viewing - An exploratory study. Appetite. 2018. 123:160–168. doi:10.1016/j.appet.2017.12.019 29273466 | Study design; Outcome
94 | Crozier, SR, Inskip, HM, Godfrey, KM, Cooper, C, Robinson, SM. Nausea and vomiting in early pregnancy: Effects on food intake and diet quality. Matern Child Nutr. 2017. 13(4):e12389. doi:10.1111/mcn.12389 27896913 | Outcome
95 | da Mota Santana, Jerusa, Alves de Oliveira Queiroz, Valterlinda, Monteiro Brito, Sheila, Barbosa dos Santos, Djanilson, Oliveira Assis, Ana Marlucia, Marlucia Oliveira Assis, Ana. FOOD CONSUMPTION PATTERNS DURING PREGNANCY: A LONGITUDINAL STUDY IN A REGION OF THE NORTH EAST OF BRAZIL. Nutricion Hospitalaria. 2015. 32:130–138. doi:10.3305/nh.2015.32.1.8970 26262707 | Intervention/Exposure; Outcome
96 | Daly, RM, Brown, M, Bass, S, Kukuljan, S, Nowson, C. Calcium- and vitamin D3-fortified milk reduces bone loss at clinically relevant skeletal sites in older men: a 2-year randomized controlled trial. J Bone Miner Res. 2006. 21:397–405. doi:10.1359/jbmr.051206 16491287 | Intervention/exposure
97 | Daly, RM, Gianoudis, J, De Ross, B, O'Connell, SL, Kruger, M, Schollum, L, Gunn, C. Effects of a multinutrient-fortified milk drink combined with exercise on functional performance, muscle strength, body composition, inflammation, and oxidative stress in middle-aged women: a 4-month, double-blind, placebo-controlled, randomized trial. Am J Clin Nutr. 2020. 112:427–446. doi:10.1093/ajcn/nqaa126. 32469393 | Int/exp: Not included bev type
98 | Daly, RM, Gianoudis, J, De Ross, B, O'Connell, SL, Kruger, M, Schollum, L, Gunn, C. Effects of a multinutrient-fortified milk drink combined with exercise on functional performance, muscle strength, body composition, inflammation, and oxidative stress in middle-aged women: a 4-month, double-blind, placebo-controlled, randomized trial. Am J Clin Nutr. 2020. 112:427–446. doi:10.1093/ajcn/nqaa126. 32469393 | Int/Exp: Not relevant
99 | Daly, RM, Nowson, CA. Long-term effect of calcium-vitamin D(3) fortified milk on blood pressure and serum lipid concentrations in healthy older men. Eur J Clin Nutr. 2009. 63:993–1000. doi:10.1038/ejcn.2008.79 19156159 | Intervention/exposure; Comparator
100 | Daly, RM, Petrass, N, Bass, S, Nowson, CA. The skeletal benefits of calcium- and vitamin D3-fortified milk are sustained in older men after withdrawal of supplementation: an 18-mo follow-up study. Am J Clin Nutr. 2008. 87:771–7. doi:10.1093/ajcn/87.3.771 18326617 | Intervention/exposure
101 | Daniel MM, Liboredo JC, Anastácio LR, Souza TCM, Oliveira LA, Della Lucia CM, Ferreira LG. Incidence and Associated Factors of Weight Gain During the Covid-19 Pandemic. Front Nutr. 2022. 9:818632. doi:10.3389/fnut.2022.818632.35284434 | Study design; Int/Exp: Not relevant
102 | Danileviciute, A, Grazuleviciene, R, Vencloviene, J, Paulauskas, A, Nieuwenhuijsen, MJ. Exposure to drinking water trihalomethanes and their association with low birth weight and small for gestational age in genetically susceptible women. Int J Environ Res Public Health. 2012. 9:4470–85. doi:10.3390/ijerph9124470 23222181 | Population
103 | Darnai, G, Plózer, E, Perlaki, G, Orsi, G, Nagy, SA, Horváth, R, Schwarcz, A, Kovács, N, Altbäcker, A, Janszky, J, Clemens, Z. Milk and dairy consumption correlates with cerebral cortical as well as cerebral white matter volume in healthy young adults. Int J Food Sci Nutr. 2015. 66:826–9. doi:10.3109/09637486.2015.1093609 26436708 | Outcome
104 | Davis, JN, Shearrer, GE, Tao, W, Hurston, SR, Gunderson, EP. Dietary variables associated with substantial postpartum weight retention at 1-year among women with GDM pregnancy. BMC Obes. 2017. 4:31. doi:10.1186/s40608-017-0166-0 28794888 | Other; Included in GWG/PPWL search
105 | Dayeon, Shin, Kyung Won, Lee, Song, WonO. Pre-Pregnancy Weight Status Is Associated with Diet Quality and Nutritional Biomarkers during Pregnancy. Nutrients. 2016. 8:162. doi:10.3390/nu8030162 26978398 | Intervention/Exposure; Outcome
106 | de Jersey, SJ, Nicholson, JM, Callaway, LK, Daniels, LA. An observational study of nutrition and physical activity behaviours, knowledge, and advice in pregnancy. BMC Pregnancy Childbirth. 2013. 13:115. doi:10.1186/1471-2393-13-115 23688111 | Outcome; Population
107 | De B, Shrivastav A, Das T, Goswami TK. Physicochemical and nutritional assessment of soy milk and soymilk products and comparative evaluation of their effects on blood gluco-lipid profile. Applied Food Research. 2022;2(2):100146. doi:10.1016/j.afres.2022.100146 | Int/exp: Not included bev type
108 | Descarpentrie A, Bernard JY, Vandentorren S, Melchior M, Galéra C, Chia A, Chong MF, Charles MA, Heude B, Lioret S. Prospective associations of lifestyle patterns in early childhood with socio-emotional and behavioural development and BMI: An outcome-wide analysis of the EDEN mother-child cohort.. Paediatr Perinat Epidemiol. 2023. 37(1):69–80. doi:10.1111/ppe.12926.36146899 | Int/Exp: Not relevant
109 | Dominguez, LigiaJ, Donat-Vargas, Carolina, Banegas, JoséR, Barbagallo, Mario, Rodríguez-Artalejo, Fernando, Guallar-Castillón, Pilar. Adherence to a Healthy Beverage Score Is Associated with Lower Frailty Risk in Older Adults. Nutrients. 2022. 14:N.PAG–N.PAG. doi:10.3390/nu14183861. | Duplicate; Other; duplicate of refid 35843637
110 | Dominguez, LJ, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, Gea, A, Barbagallo, M, Bes-Rastrollo, M. Fast food consumption and gestational diabetes incidence in the SUN project. PLoS One. 2014. 9:e106627. doi:10.1371/journal.pone.0106627 25215961 | Intervention/Exposure; Outcome
111 | Donazar-Ezcurra, M, Lopez-Del Burgo, C, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, de Irala, J, Bes-Rastrollo, M. Soft drink consumption and gestational diabetes risk in the SUN project. Clin Nutr. 2018. 37:638–645. doi:10.1016/j.clnu.2017.02.005 28262323 | Outcome
112 | Dong, Xing-Xuan, Wang, Rui-Rui, Liu, Jie-Yu, Ma, Qing-Hua, Pan, Chen-Wei. Habitual tea consumption and 5-year incident metabolic syndrome among older adults: a community-based cohort study. BMC Geriatrics. 2021. 21:1–9. doi:10.1186/s12877-021-02707-8.33388045 | Duplicate
113 | Dong, Xing-Xuan, Wang, Rui-Rui, Liu, Jie-Yu, Ma, Qing-Hua, Pan, Chen-Wei. Habitual tea consumption and 5-year incident metabolic syndrome among older adults: a community-based cohort study. BMC Geriatrics. 2021. 21:1–9. doi:10.1186/s12877-021-02707-8.33388045 | Other; Duplicate
114 | Drapeau V, Harvey AA, Jacob R, Provencher V, Panahi S. The impact of a family webbased nutrition intervention to increase fruit, vegetable, and dairy intakes: a single-blinded randomized family clustered intervention.. NutrJ. 2022. 21 (1 ):75. doi:10.1186/s12937-02200825-6.36539753 | Int/Exp: Not relevant
115 | Drouin-Chartier, JP, Li, Y, Ardisson Korat, AV, Ding, M, Lamarche, B, Manson, JE, Rimm, EB, Willett, WC, Hu, FB. Changes in dairy product consumption and risk of type 2 diabetes: results from 3 large prospective cohorts of US men and women. Am J Clin Nutr. 2019. 110:1201–1212. doi:10.1093/ajcn/nqz180 31504094 | Intervention/exposure; Outcome
116 | Dubois L, Bedard B, Goulet D, Prud'homme D, Tremblay RE, Boivin M. Eating behaviors, dietary patterns and weight status in emerging adulthood and longitudinal associations with eating behaviors in early childhood.. Int J Behav Nutr Phys Act. 2022;19(1):139. doi: 10.1186/s12966-022-01376-z.36384744 | Int/Exp: Not relevant; Outcome
117 | Dubois, Lise, Bedard, Brigitte, Goulet, Danick, Prud'homme, Denis, Tremblay, RichardE, Boivin, Michel. Eating behaviors, dietary patterns and weight status in emerging adulthood and longitudinal associations with eating behaviors in early childhood. International Journal of Behavioral Nutrition & Physical Activity. 2022. 19:1–11. doi: 10.1186/s12966-022-01376-z.34991593 | Int/Exp: Not relevant
118 | Duthie, SJ, Duthie, GG, Russell, WR, Kyle, JAM, Macdiarmid, Jl, Rungapamestry, V, Stephen, S, Megias-Baeza, C, Kaniewska, J J, Shaw, L, Milne, L, Bremner, D, Ross, K, Morrice, P, Pirie, LP, Horgan, G, Bestwick, CS. Effect of increasing fruit and vegetable intake by dietary intervention on nutritional biomarkers and attitudes to dietary change: a randomised trial. EurJNutr. 2018. 57:1855–1872. doi:10.1007/s00394-017-1469-0 | Intervention/exposure
119 | Edwards, AJ, Vinyard, BT, Wiley, ER, Brown, ED, Collins, JK, Perkins-Veazie, P, Baker, RA, Clevidence, BA. Consumption of watermelon juice increases plasma concentrations of lycopene and beta-carotene in humans. J Nutr. 2003. 133:1043–50. doi:10.1093/jn/133.4.1043 12672916 | Outcome
120 | El-Elimat, Tamam, Qasem, Wala'aM, Al-Sawalha, NourA, AbuAISamen, MahmoudM, Munaiem, RamziT, Al-Qiam, Reema, Al Sharie, AhmedH, Al-Qiam, Reema. A Prospective Non-Randomized Open-Label Comparative Study of The Effects of Matcha Tea on Overweight and Obese Individuals: A Pilot Observational Study. Plant Foods for Human Nutrition. 2022. 77:447–454. doi: 10.1007/s11130-022-00998-9.35921023 | Duplicate; Other; duplicate of ref18454
121 | Elliott, LauraJ, Keown-Stoneman, CharlesDG, Birken, Catherines, Jenkins, DavidJA, Borkhoff, CorneliaM, Maguire, JonathonL. Vegetarian Diet, Growth, and Nutrition in Early Childhood: A Longitudinal Cohort Study. Pediatrics. 2022. 149:44–55. doi:10.1542/peds.2021052598. | Int/Exp: Not relevant; Other; Duplicate
122 | Elvebakk, T, Mostad, IL, Morkved, S, Salvesen, K. Dietary intakes and dietary quality during pregnancy in women with and without gestational diabetes mellitus—a Norwegian longitudinal study. Nutrients. 2018. 10(11):1811. doi: 10.3390/nu10111811 30463394 | Outcome
123 | Elvebakk, T, Mostad, IL, Morkved, S, Salvesen, KA, Stafne, SN. Dietary Intakes and Dietary Quality during Pregnancy in Women with and without Gestational Diabetes Mellitus-A Norwegian Longitudinal Study. Nutrients. 2018. 10(11 ):1811. doi: 10.3390/nu10111811 30463394 | Outcome; Duplicate
124 | Englund-Ogge, L, Brantsaeter, AL, Haugen, M, Sengpiel, V, Khatibi, A, Myhre, R, Myking, S, Meltzer, HM, Kacerovsky, M, Nilsen, RM, Jacobsson, B. Association between intake of artificially sweetened and sugar-sweetened beverages and preterm delivery: a large prospective cohort study. Am J Clin Nutr. 2012. 96:552–9. doi: 10.3945/ajcn.111.031567 22854404 | Outcome; Population
125 | Eny, KM, Jeyakumar, N, Dai, DWH, Maguire, JL, Parkin, PC, Birken, CS. Sugar-containing beverage consumption and cardiometabolic risk in preschool children. Prev Med Rep. 2020. 17:101054. doi:10.1016/j.pmedr.2020.101054.32021763 | Study design
126 | Ericson, U, Brunkwall, L, Alves Dias, J, Drake, I, Hellstrand, S, Gullberg, B, Sonestedt, E, Nilsson, PM, Wirfält, E, Orho-Melander, M. Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmö Diet and Cancer cohort. European Journal of Nutrition. 2019. 58:1801–1814. doi:10.1007/s00394-018-1727-9.29855685 | Int/Exp: Not relevant
127 | Ezendam, NP, Evans, AE, Stigler, MH, Brug, J, Oenema, A. Cognitive and home environmental predictors of change in sugar-sweetened beverage consumption among adolescents. Br J Nutr. 2010. 103:768–74. doi:10.1017/s0007114509992297 20003610 | Outcome
128 | Fang, J, Gong, C, Wan, Y, Xu, Y, Tao, F, Sun, Y. Polygenic risk, adherence to a healthy lifestyle, and childhood obesity. Pediatric Obesity. 2019. 14(4):e12489. doi:10.1111/ijpo.12489.30515989 | Study design
129 | Fernandez-Cao, JC, Arija, V, Aranda, N, Bullo, M, Basora, J, Martínez-González, MA, Díez-Espino, J, Salas-Salvadó, J. Heme iron intake and risk of new-onset diabetes in a Mediterranean population at high risk of cardiovascular disease: an observational cohort analysis. BMC Public Health. 2013. 13:1042. doi:10.1186/1471-2458-13-1042 24188615 | Intervention/exposure; Outcome
130 | Ferranti, EP, Hartman, TJ, Elliott, AJ, Mitchell, DC, Angal, J, Nickleach, D, Bellissimo, M, Breslow, R. Diet Quality of Pregnant American Indian Women in the Northern Plains. Prev Chronic Dis. 2019. 16:E53. doi:10.5888/pcd16.180536 31022368 | Outcome
131 | Feskanich, D, Bischoff-Ferrari, HA, Frazier, AL, Willett, WC. Milk consumption during teenage years and risk of hip fractures in older adults. JAMA Pediatr. 2014. 168:54–60. doi:10.1001/jamapediatrics.2013.3821 24247817 | Outcome; Other; no sig testing of relevant results
132 | Flynn, AC, Thompson, JMD, Dalrymple, KV, Wall, C, Begum, S, Pallippadan Johny, J, Cutfield, WS, North, R, McCowan, LME, Godfrey, KM, Mitchell, EA, Poston, L. Childhood dietary patterns and body composition at age 6 years: the Children of SCOPE study. Br J Nutr. 2020. 124:1–21. doi:10.1017/s0007114520000628. | Study design; Int/Exp: Not relevant
133 | Forsum, Elisabet, Henriksson, Pontus, Löf, Marie. The Two-Component Model for Calculating Total Body Fat from Body Density: An Evaluation in Healthy Women before, during and after Pregnancy. Nutrients. 2014. 6:5888–5899. doi:10.3390/nu6125888 25526240 | Intervention/Exposure
134 | Foscolou, A, Magriplis, E, Tyrovolas, S, Soulis, G, Bountziouka, V, Mariolis, A, Piscopo, S, Valacchi, G, Anastasiou, F, Gotsis, E, Metallinos, G, Tyrovola, D, Polystipioti, A, Polychronopoulos, E, Matalas, AL, Lionis, C, Zeimbekis, A, Tur, JA, Sidossis, LS, Panagiotakos, D. Lifestyle determinants of healthy ageing in a Mediterranean population: The multinational MEDIS study. Exp Gerontol. 2018. 110:35–41. doi:10.1016/j.exger.2018.05.008 29763722 | Intervention/exposure
135 | Fowles, ER, Walker, LO. Correlates of dietary quality and weight retention in postpartum women. J Community Health Nurs. 2006. 23:183–97. doi:10.1207/s15327655jchn2303_5 16863403 | Intervention/Exposure
136 | Freitas-Vilela, AA, Smith, AD, Kac, G, Pearson, RM, Heron, J, Emond, A, Hibbeln, JR, Castro, MB, Emmett, PM. Dietary patterns by cluster analysis in pregnant women: relationship with nutrient intakes and dietary patterns in 7-year-old offspring. Matern Child Nutr. 2017. 13(2):e12353. doi:10.1111/mcn.12353 27723265 | Outcome; Population
137 | Funatsu, K, Yamashita, T, Nakamura, H. Effect of coffee intake on blood pressure in male habitual alcohol drinkers. Hypertens Res. 2005. 28:521–7. doi:10.1291/hypres.28.521 16231758 | EXCLUDE
138 | Fung TT, Pan A, Hou T, Long-Term Change in Diet Quality Is Associated with Body Weight Change in Men and Women [published correction appears in J Nutr. 2016 Sep;146(9):1813. doi: 10.3945/jn.116.238576]. J Nutr. 2015;145(8):1850–1856. doi:10.3945/jn.114.208785 26084363 | Int/Exp: Not relevant
139 | Gaeini, Z, Bahadoran, Z, Mirmiran, P, Azizi, F. Tea, coffee, caffeine intake and the risk of cardio-metabolic outcomes: findings from a population with low coffee and high tea consumption. Nutr Metab (Lond). 2019. 16:28. doi:10.1186/s12986-019-0355-6 31073321 | Outcome
140 | Gago C, Aftosmes-Tobio A, Beckerman-Hsu JP, Oddleifson C, Garcia EA, Lansburg K, Figueroa R, Yu X, Kitos N, Torrico M, Leonard J, Jurkowski JK, Mattei J, Kenney EL, Haneuse S, Davison KK. Evaluation of a cluster-randomized controlled trial: Communities for Healthy Living, family-centered obesity prevention program for Head Start parents and children. Int J Behav Nutr Phys Act. 2023;20(1):4. doi:10.1186/s12966-022-01400-2.36631869 | Int/Exp: Not relevant
141 | Gallegos, D, Do, H, To, QG, Vo, B, Goris, J, Alraman, H. The effectiveness of living well multicultural-lifestyle management program among ethnic populations in Queensland, Australia. Health Promot J Austr. 2021. 32:84–95. doi:10.1002/hpja.329.32053254 | Study design; Int/Exp: Not relevant; Comparator
142 | Garcia DO, Morrill KE, Aceves B, Feasibility and acceptability of a beverage intervention for Hispanic adults: results from a pilot randomized controlled trial. Public Health Nutr. 2019;22(3):542–552. doi:10.1017/S1368980018003051 30451147 | EXCLUDE
143 | García-Cordero J, Sierra-Cinos JL, Seguido MA, González-Rámila S, Mateos R, Bravo-Clemente L, Sarriá B. Regular Consumption of Green Coffee Phenol, Oat β-Glucan and Green Coffee Phenol/Oat β-Glucan Supplements Does Not Change Body Composition in Subjects with Overweight and Obesity. Foods. 2022;11(5):679. doi:10.3390/foods11050679.35267313 | Int/Exp: Not relevant
144 | Gaskins, AJ, Rich-Edwards, JW, Williams, PL, Toth, TL, Missmer, SA, Chavarro, JE. Prepregnancy caffeine and caffeinated beverage intake and risk of spontaneous abortion. Eur J Nutr. 2018. 57:107–117. doi:10.1007/s00394-016-1301-2 27573467 | Outcome
145 | Ghasemi, V, Kheirkhah, M, Vahedi, M. The Effect of Herbal Tea Containing Fenugreek Seed on the Signs of Breast Milk Sufficiency in Iranian Girl Infants. Iran Red Crescent Med J. 2015. 17:e21848. doi:10.5812/ircmj.21848 26430522 | Population
146 | Ghizi AC da S, de Almeida Silva M, Moraes FS de A, Kefir improves blood parameters and reduces cardiovascular risks in patients with metabolic syndrome. PharmaNutrition. 2021;16:100266. doi:10.1016/j.phanu.2021.100266 | Int/exp: Not included bev type
147 | Gillman, MW, Rifas-Shiman, SL, Fernandez-Barres, S, Kleinman, K, Taveras, EM, Oken, E. Beverage Intake During Pregnancy and Childhood Adiposity. Pediatrics. 2017. 140(2):e20170031. doi:10.1542/peds.2017-0031 28689188 | Outcome; Population
148 | Giroux, I, Inglis, SD, Lander, S, Gerrie, S, Mottola, MF. Dietary intake, weight gain, and birth outcomes of physically active pregnant women: a pilot study. Appl Physiol Nutr Metab. 2006. 31:483–9. doi:10.1139/h06-024 17111001 | Intervention/Exposure
149 | Gkouskou KG, Georgiopoulos G, Vlastos I, CYP1A2 polymorphisms modify the association of habitual coffee consumption with appetite, macronutrient intake, and body mass index: results from an observational cohort and a cross-over randomized study. Int J Obes (Lond). 2022;46(1):162–168. doi:10.1038/s41366-021-00972-6 34564706 | Study design
150 | Gonçalinho GHF, Nascimento JRO, Mioto BM, Effects of Coffee on Sirtuin-1, Homocysteine, and Cholesterol of Healthy Adults: Does the Coffee Powder Matter?. J Clin Med. 2022;11(11):2985. Published 2022 May 25. doi:10.3390/jcm11112985 35683374 | Comparator
151 | Gonzalez, HF, Malpeli, A, Mansur, JL, De Santiago, S, Etchegoyen, GS. Changes in body composition in lactating adolescent mothers. Arch Latinoam Nutr. 2005. 55:252–6.16454051 | Intervention/Exposure
152 | Gonzalez-Palacios S, Navarrete-Muñoz EM, García-de-la-Hera M, Sugar-Containing Beverages Consumption and Obesity in Children Aged 4–5 Years in Spain: the INMA Study. Nutrients. 2019;11(8):1772. Published 2019 Aug 1. doi:10.3390/nu11081772 31374897 | Study design
153 | Grandjean, AC, Reimers, KJ, Haven, MC, Curtis, GL. The effect on hydration of two diets, one with and one without plain water. J Am Coll Nutr. 2003. 22:165–73. doi:10.1080/07315724.2003.10719290 12672713 | EXCLUDE
154 | Grazuleviciene, R, Nieuwenhuijsen, MJ, Vencloviene, J, Kostopoulou-Karadanelli, M, Krasner, SW, Danileviciute, A, Balcius, G, Kapustinskiene, V. Individual exposures to drinking water trihalomethanes, low birth weight and small for gestational age risk: a prospective Kaunas cohort study. Environ Health. 2011. 10:32. doi: 10.1186/1476-069x-10-32 21501533 | Intervention/Exposure; Outcome
155 | Greenberg, JA, Axen, KV, Schnoll, R, Boozer, CN. Coffee, tea and diabetes: the role of weight loss and caffeine. IntJ Obes (bond). 2005. 29:1121–9. doi: 10.1038/sj.ijo.0802999 | Study design
156 | Grieger, JA, Nowson, CA. Use of calcium, folate, and vitamin D_3_-fortified milk for 6 months improves nutritional status but not bone mass or turnover, in a group of Australian aged care residents. J Nutr Elder. 2009. 28:236–54. doi: 10.1080/01639360903140130 21184368 | Study design; Intervention/exposure
157 | Grijalva-Avila, J, Villanueva-Fierro, I, Lares-Asseff, I, Chairez-Hernandez, I, Rivera-Sanchez, G, Martinez-Estrada, S, Martinez-Rivera, I, Quinones, LA, Loera-Castaneda, V. Milk intake and IGF-1 rs6214 polymorphism as protective factors to obesity. Int J Food Sci Nutr. 2020. 71:388–393. doi: 10.1080/09637486.2019.1666805.31530040 | Study design
158 | Grosso, LM, Rosenberg, KD, Belanger, K, Saftlas, AF, Leaderer, B, Bracken, MB. Maternal caffeine intake and intrauterine growth retardation. Epidemiology. 2001. 12:447–55. doi:10.1097/00001648-200107000-00015 11428387 | Outcome; Population
159 | Grosso, LM, Rosenberg, KD, Belanger, K, Saftlas, AF, Leaderer, B, Bracken, MB. Maternal caffeine intake and intrauterine growth retardation. Epidemiology. 2001. 12:447–55. doi:10.1097/00001648-200107000-00015 11428387 | Intervention/exposure; Outcome
160 | Groth, SW, Stewart, PA, Ossip, DJ, Block, RC, Wixom, N, Fernandez, ID. Micronutrient Intake Is Inadequate for a Sample of Pregnant African-American Women. J Acad Nutr Diet. 2017. 117:589–598. doi: 10.1016/j.jand.2016.11.011 28065633 | Intervention/Exposure
161 | Grundt, Jacob Holter, Nakling, Jakob, Eide, Geir Egil, Markestad, Trond. Possible relation between maternal consumption of added sugar and sugar-sweetened beverages and birth weight - time trends in a population. BMC Public Health. 2012. 12:901-901. doi:10.1186/1471-2458-12901 23095173 | Outcome; Population
162 | Grundt, JH, Nakling, J, Eide, GE, Markestad, T. Possible relation between maternal consumption of added sugar and sugar-sweetened beverages and birth weight-time trends in a population. BMC Public Health. 2012. 12:901. doi: 10.1186/1471-2458-12-901 23095173 | Outcome; Population
163 | Haghighatdoost, F, Azadbakht, L. Probiotic soy milk and anthropometric measures: Is probiotic soy milk beyond soy milk?. ARYA Atheroscler. 2015. 11:265–6.26715930 | Study design
164 | Haire-Joshu, D, Schwarz, C, Jacob, R, Kristen, P, Johnston, S, Quinn, K, Tabak, R. Raising Well at Home: a pre-post feasibility study of a lifestyle intervention for caregivers and their child with obesity. Pilot Feasibility Stud. 2020. 6:149. doi: 10.1186/s40814-020-00692-0.33042569 | Study design
165 | Haire-Joshu, D, Yount, BW, Budd, EL, Schwarz, C, Schermbeck, R, Green, S, Elliott, M. The quality of school wellness policies and energy-balance behaviors of adolescent mothers. Prev Chronic Dis. 2011. 8:A34.21324248 | Outcome
166 | Haire-Joshu, DL, Schwarz, CD, Peskoe, SB, Budd, EL, Brownson, RC, Joshu, CE. A group randomized controlled trial integrating obesity prevention and control for postpartum adolescents in a home visiting program. Int J Behav Nutr Phys Act. 2015. 12:88. doi: 10.1186/s12966-015-0247-8 26112041 | Intervention/Exposure
167 | Halicioglu, O, Sutcuoglu, S, Koc, F, Ozturk, C, Albudak, E, Colak, A, Sahin, E, AsikAkman, S. Vitamin B12 and folate statuses are associated with diet in pregnant women, but not with anthropometric measurements in term newborns. J Matern Fetal Neonatal Med. 2012. 25:1618–21. doi:10.3109/14767058.2011.648244 22185230 | Intervention/Exposure
168 | Halldorsson, Tl, Strom, M, Petersen, SB, Olsen, SF. Intake of artificially sweetened soft drinks and risk of preterm delivery: a prospective cohort study in 59,334 Danish pregnant women. Am J Clin Nutr. 2010. 92:626–33. doi: 10.3945/ajcn.2009.28968 20592133 | Outcome; Population
169 | Hedrick, VE, Davy, BM, You, W, Porter, KJ, Estabrooks, PA, Zoellner, JM. Dietary quality changes in response to a sugar-sweetened beverage-reduction intervention: results from the Talking Health randomized controlled clinical trial. Am J Clin Nutr. 2017. 105:824–833. doi:10.3945/ajcn.116.144543 28251935 | Outcome
170 | Heppe, DH, van Dam, RM, Willemsen, SP, den Breeijen, H, Raat, H, Hofman, A, Steegers, EA, Jaddoe, VW. Maternal milk consumption, fetal growth, and the risks of neonatal complications: the Generation R Study. Am J Clin Nutr. 2011. 94:501–9. doi:10.3945/ajcn.111.013854 21697074 | Outcome; Population
171 | Herber, C, Bogler, L, Subramanian, SV, Vollmer, S. Association between milk consumption and child growth for children aged 6–59 months. Sci Rep. 2020. 10:6730. doi:10.1038/s41598-020-63647-8.32317668 | Country
172 | Higgins, KA, Mattes, RD. A randomized controlled trial contrasting the effects of 4 low-calorie sweeteners and sucrose on body weight in adults with overweight or obesity. American Journal of Clinical Nutrition. 2019. 109:1288–1301. doi:10.1093/ajcn/nqy381.30997499 | Int/Exp: Not relevant
173 | Hillesund, ER, Bere, E, Haugen, M, Overby, NC. Development of a New Nordic Diet score and its association with gestational weight gain and fetal growth - a study performed in the Norwegian Mother and Child Cohort Study (MoBa). Public Health Nutr. 2014. 17:1909–18. doi:10.1017/s1368980014000421 24685309 | Intervention/Exposure
174 | Hinkle S, Li M, Grewal J, Beverage Intake in U.S. Women Across Pregnancy and Gestational Diabetes Risk (P11–010-19). Curr Dev Nutr. 2019;3(Suppl 1):nzz048.P11–010-19. Published 2019 Jun 13. doi:10.1093/cdn/nzz048.P11-010-19 | Pub status
175 | Hinkle, SN, Laughon, SK, Catov, JM, Olsen, J, Bech, BH. First trimester coffee and tea intake and risk of gestational diabetes mellitus: a study within a national birth cohort. Bjog. 2015. 122:420–8. doi:10.1111/1471-0528.12930 24947484 | Outcome
176 | Hinkle, SN, Rawal, S, Bjerregaard, AA, Halldorsson, TI, Li, M, Ley, SH, Wu, J, Zhu, Y, Chen, L, Liu, A, Grunnet, LG, Rahman, ML, Kampmann, FB, Mills, JL, Olsen, SF, Zhang, C. A prospective study of artificially sweetened beverage intake and cardiometabolic health among women at high risk. Am J Clin Nutr. 2019. 110:221–232. doi:10.1093/ajcn/nqz094.31172169 | Study design; EXLUDE - All other health status criteria
177 | Hirota, T, Kusu, T, Hirota, K. Improvement of nutrition stimulates bone mineral gain in Japanese school children and adolescents. Osteoporos Int. 2005. 16:1057–64. doi:10.1007/s00198-004-1804-1 15690108 | Outcome
178 | Hodge, AM, O'Dea, K, English, DR, Giles, GG, Flicker, L. Dietary patterns as predictors of successful ageing. J Nutr Health Aging. 2014. 18:221–7. doi:10.1007/s12603-013-0405-0 24626747 | Intervention/exposure
179 | Hodgson, JM, Croft, KD, Woodman, RJ, Puddey, IB, Fuchs, D, Draijer, R, Lukoshkova, E, Head, GA. Black tea lowers the rate of blood pressure variation: a randomized controlled trial. Am J Clin Nutr. 2013. 97:943–50. doi:10.3945/ajcn.112.051375 23553154 | Comparator; Outcome
180 | Hoffman, CS, Mendola, P, Savitz, DA, Herring, AH, Loomis, D, Hartmann, KE, Singer, PC, Weinberg, HS, Olshan, AF. Drinking water disinfection by-product exposure and fetal growth. Epidemiology. 2008. 19:729–37. doi:10.1097/EDE.0b013e3181812bd4 18633330 | Outcome; Population
181 | Hohoff E, Perrar I, Jankovic N, Alexy U. Dairy intake and long-term body weight status in German children and adolescents: results from the DONALD study. Eur J Nutr. 2022;61(2):1087–1096. doi:10.1007/s00394-021-02715-9 34718860 | Int/Exp: Not relevant
182 | Hopenhayn, C, Ferreccio, C, Browning, SR, Huang, B, Peralta, C, Gibb, H, Hertz-Picciotto, I. Arsenic exposure from drinking water and birth weight. Epidemiology. 2003. 14:593–602. doi:10.1097/01.ede.0000072104.65240.69 14501275 | Intervention/Exposure; Population
183 | Hoppe, C, Udam, TR, Lauritzen, L, Mølgaard, C, Juul, A, Michaelsen, KF. Animal protein intake, serum insulin-like growth factor I, and growth in healthy 2.5-y-old Danish children. Am J Clin Nutr. 2004. 80:447–52. doi:10.1093/ajcn/80.2.447 15277169 | Study design
184 | Hrolfsdottir L, Halldorsson TI, Birgisdottir BE, Hreidarsdottir IT, Hardardottir H, Gunnarsdottir I. Development of a dietary screening questionnaire to predict excessive weight gain in pregnancy. Matern Child Nutr. 2019;15(1):e12639. doi:10.1111/mcn.12639 30033533 | Intervention/Exposure
185 | Hrolfsdottir L, Halldorsson TI, Birgisdottir BE, Hreidarsdottir IT, Hardardottir H, Gunnarsdottir I. Development of a dietary screening questionnaire to predict excessive weight gain in pregnancy. Matern Child Nutr. 2019;15(1):e12639. doi:10.1111/mcn.12639 30033533 | Duplicate; Other
186 | Hrolfsdottir, L, Rytter, D, Hammer Bech, B, Brink Henriksen, T, Danielsen, I, Steingrimsdottir, L, Olsen, SF, Halldorsson, TI. Maternal milk consumption, birth size and adult height of offspring: a prospective cohort study with 20 years of follow-up. Eur J Clin Nutr. 2013. 67:1036–41. doi:10.1038/ejcn.2013.151 24002041 | Outcome
187 | Hsia, DS, Zhang, DJ, Beyl, RS, Greenway, FL, Khoo, C. Effect of daily consumption of cranberry beverage on insulin sensitivity and modification of cardiovascular risk factors in adults with obesity: a pilot, randomised, placebo-controlled study. Br J Nutr. 2020. 124:577–585. doi:10.1017/s0007114520001336.32301407 | Int/Exp: Not relevant; Comparator
188 | Huang, L, Lerro, C, Yang, T, Li, J, Qiu, J, Qiu, W, He, X, Cui, H, Lv, L, Xu, R, Xu, X, Huang, H, Liu, Q, Zhang, Y. Maternal tea consumption and the risk of preterm delivery in urban China: a birth cohort study. BMC Public Health. 2016. 16:456. doi:10.1186/s12889-016-3100-3 27246202 | Outcome
189 | Huang, L, Lerro, C, Yang, T, Li, J, Qiu, J, Qiu, W, He, X, Cui, H, Lv, L, Xu, R, Xu, X, Huang, H, Liu, Q, Zhang, Y. Maternal tea consumption and the risk of preterm delivery in urban China: a birth cohort study. BMC Public Health. 2016. 16:456. doi:10.1186/s12889-016-3100-3 27246202 | Outcome; Other; Captured in GWG/PPWL search
190 | Huseinovic, E, Winkvist, A, Bertz, F, Brekke, HK. Changes in food choice during a successful weight loss trial in overweight and obese postpartum women. Obesity (Silver Spring). 2014. 22:2517–23. doi:10.1002/oby.20895 25234605 | Intervention/Exposure
191 | Hwang, JY, Lee, H, Ko, A, Han, CJ, Chung, HW, Chang, N. Dietary changes in Vietnamese marriage immigrant women: The KoGES follow-up study. Nutr Res Pract. 2014. 8:319–26. doi:10.4162/nrp.2014.8.3.319 24944778 | Outcome; Country
192 | Hyson, D, Studebaker-Hallman, D, Davis, PA, Gershwin, ME. Apple juice consumption reduces plasma low-density lipoprotein oxidation in healthy men and women. J Med Food. 2000. 3:159–66. doi:10.1089/jmf.2000.3.159 19236172 | Outcome
193 | Igarashi M, Nogawa S, Hachiya T, Association between Dietary Behaviors and BMI Stratified by Sex and the ALDH2 rs671 Polymorphism in Japanese Adults. Nutrients. 2022;14(23):5116. Published 2022 Dec 1. doi:10.3390/nu14235116 36501145 | Study design
194 | Igarashi, Y, Obara, T, Ishikuro, M, Matsubara, H, Shigihara, M, Metoki, H, Kikuya, M, Sameshima, Y, Tachibana, H, Maeda-Yamamoto, M, Kuriyama, S. Randomized controlled trial of the effects of consumption of 'Yabukita' or 'Benifuuki' encapsulated tea-powder on low-density lipoprotein cholesterol level and body weight. Food Nutr Res. 2017. 61:1334484. doi:10.1080/16546628.2017.1334484 28680384 | Intervention/exposure
195 | Iszatt, N, Nieuwenhuijsen, MJ, Bennett, JE, Toledano, MB. Trihalomethanes in public drinking water and stillbirth and low birth weight rates: an intervention study. Environ Int. 2014. 73:434–9. doi:10.1016/j.envint.2014.08.006 25244706 | Intervention/Exposure; Outcome; Population
196 | Jardí, C, Aparicio, E, Bedmar, C, Aranda, N, Abajo, S, March, G, Basora, J, Arija, V, Study Group, TE. Food Consumption during Pregnancy and Post-Partum. ECLIPSES Study. Nutrients. 2019. 11(10):2447. doi:10.3390/nu11102447 31615024 | Intervention/exposure; Outcome
197 | Jarosz, M, Wierzejska, R, Siuba, M. Maternal caffeine intake and its effect on pregnancy outcomes. Eur J Obstet Gynecol Reprod Biol. 2012. 160:156–60. doi:10.1016/j.ejogrb.2011.11.021 22142815 | Intervention/Exposure
198 | Jasim, SK, Al-Momen, H, Alqurishi, AK. Effects of excessive tea consumption on pregnancy weight gain and neonatal birth weight. Obstet Gynecol Sci. 2021. 64:34–41. doi:10.5468/ogs.20157.33249804 | Country
199 | Jen, V, Erler, NS, Tielemans, MJ, Braun, KV, Jaddoe, VW, Franco, OH, Voortman, T. Mothers' intake of sugar-containing beverages during pregnancy and body composition of their children during childhood: the Generation R Study. Am J Clin Nutr. 2017. 105:834–841. doi:10.3945/ajcn.116.147934 28275130 | Outcome; Population
200 | Jing, W, Huang, Y, Liu, X, Luo, B, Yang, Y, Liao, S. The effect of a personalized intervention on weight gain and physical activity among pregnant women in China. Int J Gynaecol Obstet. 2015. 129:138–41. doi:10.1016/j.ijgo.2014.11.014 25697965 | Intervention/Exposure
201 | Johnson, SA, Navaei, N, Pourafshar, S, Jaime, SJ, Akhavan, NS, Alvarez-Alvarado, S, Proaño, GV, Litwin, NS, Clark, EA, Foley, EM, George, KS, Elam, ML, Payton, ME, Arjmandi, BH, Figueroa, A. Effects of Montmorency Tart Cherry Juice Consumption on Cardiometabolic Biomarkers in Adults with Metabolic Syndrome: A Randomized Controlled Pilot Trial. Journal of Medicinal Food. 2020. 23:1238–1247. doi:10.1089/jmf.2019.0240.32429737 | Comparator
202 | Jurgens, T, Whelan, AM. Can green tea preparations help with weight loss?. Can Pharm J (Ott). 2014. 147:159–60. doi:10.1177/1715163514528668 24847368 | Study design
203 | Kalkwarf, HJ, Khoury, JC, Lanphear, BP. Milk intake during childhood and adolescence, adult bone density, and osteoporotic fractures in US women. Am J Clin Nutr. 2003. 77:257–65. doi:10.1093/ajcn/77.1.257 12499350 | Study design; Outcome
204 | Karandish, M, Sheikhi, L, Latifi, SM, Davoudi, I. Comparison of the effect of milk and pistachio snacks (pistacia vera) consumption on satiety status, body fat percent, and macronutrient intake in overweight or obese women: A randomized controlled trial. Obesity Medicine. 2021. 23:100338. doi:10.1016/j.obmed.2021.100338. | Int/Exp: Not relevant; Comparator; EXCLUDE
205 | Kaseb, F, Kimiagar, M, Ghafarpoor, M, Valaii, N. Effect of traditional food supplementation during pregnancy on maternal weight gain and birthweight. Int J Vitam Nutr Res. 2002. 72:389–93. doi:10.1024/0300-9831.72.6.389 12596505 | Intervention/Exposure
206 | Kay, MC, Wasser, H, Adair, LS, Thompson, AL, Siega-Riz, AM, Suchindran, CM, Bentley, ME. Consumption of key food groups during the postpartum period in low-income, non-Hispanic black mothers. Appetite. 2017. 117:161–167. doi:10.1016/j.appet.2017.06.023 28651972 | Outcome
207 | Killer, SC, Blannin, AK, Jeukendrup, AE. No evidence of dehydration with moderate daily coffee intake: a counterbalanced cross-over study in a free-living population. PLoS One. 2014. 9:e84154. doi:10.1371/journal.pone.0084154 24416202 | Intervention/exposure; EXCLUDE
208 | Kim, H, Kang, S, Jung, BM, Yi, H, Jung, JA, Chang, N. Breast milk fatty acid composition and fatty acid intake of lactating mothers in South Korea. Br J Nutr. 2017. 117:556–561. doi:10.1017/s0007114517000253 28285609 | Intervention/Exposure; Outcome
209 | Kishimoto, T, Churiki, M, Miyazato, T, Yamashiro, A, Nagasawa, Y, Shokita, H. Association between lifestyle and metabolic syndrome incidence of workers in northern Okinawa, Japan: A cohort study. Prev Med Rep. 2022;30:101995. doi:10.1016/j.pmedr.2022.101995 36203944 | Int/Exp: Not relevant
210 | Knüppel, A, Shipley, MJ, Llewellyn, CH, Brunner, EJ. Sugar intake from sweet food and beverages, common mental disorder and depression: prospective findings from the Whitehall II study. Sci Rep. 2017. 7:6287. doi:10.1038/s41598-017-05649-7 28751637 | Intervention/exposure; Outcome
211 | Konieczna, J, Morey, M, Abete, I, Bes-Rastrollo, M, Ruiz-Canela, M, Vioque, J, Gonzalez-Palacios, S, Daimiel, L, Salas-Salvadó, J, Fiol, M, Martín, V, Estruch, R, Vidal, J, Martínez-González, MA, Canudas, S, Jover, AJ, Fernández-Villa, T, Casas, R, Olbeyra, R, Buil-Cosiales, P, Babio, N, Schröder, H, Martínez, JA, Romaguera, D. Contribution of ultra-processed foods in visceral fat deposition and other adiposity indicators: Prospective analysis nested in the PREDIMED-Plus trial. Clin Nutr. 2021. 40:4290–4300. doi:10.1016/j.clnu.2021.01.019.33610419 | Int/exp: Not included bev type
212 | Konieczna, J, Morey, M, Abete, I, Bes-Rastrollo, M, Ruiz-Canela, M, Vioque, J, Gonzalez-Palacios, S, Daimiel, L, Salas-Salvadó, J, Fiol, M, Martín, V, Estruch, R, Vidal, J, Martínez-González, MA, Canudas, S, Jover, AJ, Fernández-Villa, T, Casas, R, Olbeyra, R, Buil-Cosiales, P, Babio, N, Schröder, H, Martínez, JA, Romaguera, D. Contribution of ultra-processed foods in visceral fat deposition and other adiposity indicators: Prospective analysis nested in the PREDIMED-Plus trial. Clin Nutr. 2021. 40:4290–4300. doi:10.1016/j.clnu.2021.01.019.33610419 | Int/Exp: Not relevant
213 | Kornatowski, BM, Comstock, SS. Dietary diversity is inversely correlated with pre-pregnancy body mass index among women in a Michigan pregnancy cohort. PeerJ. 2018. 6:e5526. doi:10.7717/peerj.5526 30210942 | Outcome
214 | Kruger, MC, Chan, YM, Lau, C, Lau, LT, Chin, YS, Kuhn-Sherlock, B, Schollum, LM, Todd, JM. Fortified Milk Supplementation Improves Vitamin D Status, Grip Strength, and Maintains Bone Density in Chinese Premenopausal Women Living in Malaysia. BioResearch Open Access. 2019. 8:16–24. doi:10.1089/biores.2018.0027.30842890 | Comparator
215 | Kujawska A, López Sánchez GF, Hoti F, Kujawski S, Zalewski P, Kędziora-Kornatowska K. Relationship of the Behavior of Older Participants with Body Composition Change: Results of the Second Wave of the Cognition of Older People, Education, Recreational Activities, Nutrition, Comorbidities, and Functional Capacity Studies (COPERNICUS). Nutrients. 2023;15(8):1834. Published 2023 Apr 11. doi:10.3390/nu15081834 37111053 | Duplicate
216 | Kukuljan, S, Nowson, CA, Sanders, KM, Nicholson, GC, Seibel, MJ, Salmon, J, Daly, RM. Independent and combined effects of calcium-vitamin D3 and exercise on bone structure and strength in older men: an 18-month factorial design randomized controlled trial. J Clin Endocrinol Metab. 2011. 96:955–63. doi:10.1210/jc.2010-2284 21209030 | Outcome
217 | La Foucade A, Laptiste C, Alcaraz A, The health and economic burden associated with sugar-sweetened beverage consumption in Trinidad and Tobago. Nutr Health. Published online February 12, 2023. doi:10.1177/02601060231156117 | Study design
218 | Lana, A, Rodriguez-Artalejo, F, Lopez-Garcia, E. Dairy Consumption and Risk of Frailty in Older Adults: A Prospective Cohort Study. J Am Geriatr Soc. 2015. 63:1852–60. doi:10.1111/jgs.13626 26311353 | Intervention/exposure
219 | Lane, JA, Er, V, Avery, KNL, Horwood, J, Cantwell, M, Caro, GP, Crozier, A, Smith, GD, Donovan, JL, Down, L, Hamdy, FC, Gillatt, D, Holly, J, Macefield, R, Moody, H, Neal, DE, Walsh, E, Martin, RM, Metcalfe, C. ProDiet: A Phase II Randomized Placebo-controlled Trial of Green Tea Catechins and Lycopene in Men at Increased Risk of Prostate Cancer. Cancer Prev Res (Phila). 2018. 11:687–696. doi:10.1158/1940-6207.Capr-18-0147 30309839 | Intervention/exposure; Comparator
220 | Larson, NI, Neumark-Sztainer, D, Harnack, L, Wall, M, Story, M, Eisenberg, ME. Calcium and dairy intake: Longitudinal trends during the transition to young adulthood and correlates of calcium intake. J Nutr Educ Behav. 2009. 41:254–60. doi:10.1016/j.jneb.2008.05.001 19508930 | Outcome
221 | Larsson, SC, Giovannucci, EL, Wolk, A. Sweetened Beverage Consumption and Risk of Biliary Tract and Gallbladder Cancer in a Prospective Study. J Natl Cancer Inst. 2016. 108(10):djw125. doi:10.1093/jnci/djw125 27281756 | Outcome
222 | Law, YY, Chiu, HF, Lee, HH, Shen, YC, Venkatakrishnan, K, Wang, CK. Consumption of onion juice modulates oxidative stress and attenuates the risk of bone disorders in middle-aged and post-menopausal healthy subjects. Food Funct. 2016. 7:902–12. doi:10.1039/c5fo01251a 26686359 | Intervention/exposure
223 | LeCroy, MN, Truesdale, KP, Matheson, DM, Karp, SM, Moore, SM, Robinson, TN, Berge, JM, Nicastro, HL, Thomas, AJ. Snacking characteristics and patterns and their associations with diet quality and BMI in the Childhood Obesity Prevention and Treatment Research Consortium. Public Health Nutr. 2019. 22:3189–3199. doi:10.1017/s1368980019000958.31112114 | Study design
224 | Lee, I, Bang, KS, Moon, H, Kim, J. Risk Factors for Obesity Among Children Aged 24 to 80 months in Korea: A Decision Tree Analysis. Journal of pediatric nursing. 2019. 46:e15–e23. doi:10.1016/j.pedn.2019.02.004.30773305 | Study design; Int/Exp: Not relevant
225 | Lelong H, Blacher J, Baudry J, Combination of Healthy Lifestyle Factors on the Risk of Hypertension in a Large Cohort of French Adults. Nutrients. 2019;11(7):1687. doi:10.3390/nu11071687 31340445 | Intervention/exposure; Outcome
226 | Lepsch, J, Vaz, JS, Moreira, JD, Pinto, TJ, Soares-Mota, M, Kac, G. Food frequency questionnaire as an indicator of the serum composition of essential n-3 and n-6 polyunsaturated fatty acids in early pregnancy, according to body mass index. J Hum Nutr Diet. 2015. 28:85–94. doi:10.1111/jhn.12225 24620790 | Intervention/Exposure; Outcome
227 | Leung, CW, Laraia, BA, Coleman-Phox, K, Bush, NR, Lin, J, Blackburn, EH, Adler, NE, Epel, ES. Sugary beverage and food consumption, and leukocyte telomere length maintenance in pregnant women. Eur J Clin Nutr. 2016. 70:1086–8. doi:10.1038/ejcn.2016.93 27302671 | Outcome
228 | Leung, SS, Chan, SM, Lui, S, Lee, WT, Davies, DP. Growth and nutrition of Hong Kong children aged 0–7 years. J Paediatr Child Health. 2000. 36:56–65. doi:10.1046/j.1440-1754.2000.00441.x | Intervention/exposure
229 | Li, B, Pallan, M, Liu, WJ, Hemming, K, Frew, E, Lin, R, Liu, W, Martin, J, Zanganeh, M, Hurley, K, Cheng, KK, Adab, P. The CHIRPY DRAGON intervention in preventing obesity in Chinese primaryschool-aged children: A cluster-randomised controlled trial. PLoS Medicine. 2019. 16(11):e1002971. doi:10.1371/journal.pmed.1002971.31770371 | Int/Exp: Not relevant
230 | Li, JY, Ge, JR, Chen, J, Ye, YJ, Xie, LH, Li, L, Chai, H. Clinical study on the influence of tea drinking habits on bone mineral density and osteoporosis in postmenopausal women in Fuzhou city, China. Progress in Nutrition. 2021. 23(1):e2021033. doi:10.23751/pn.v23i1.9409. | Study design
231 | Li, YF, Hu, NS, Tian, XB, Li, L, Wang, SM, Xu, XB, Wang, N, Shi, CG, Zhu, JC, Sun, JS, Bao, JH, Lang, SH, Li, CJ, Fan, DG, Zhang, L, Zhang, B, Gao, Y, He, B, Wang, JD, Zhang, SC. Effect of daily milk supplementation on serum and umbilical cord blood folic acid concentrations in pregnant Han and Mongolian women and birth characteristics in China. Asia Pac J Clin Nutr. 2014. 23:567–74. doi:10.6133/apjcn.2014.23.4.18 25516314 | Outcome; Population
232 | Libuda, L, Alexy, U, Buyken, AE, Sichert-Hellert, W, Stehle, P, Kersting, M. Consumption of sugar-sweetened beverages and its association with nutrient intakes and diet quality in German children and adolescents. Br J Nutr. 2009. 101:1549–57. doi:10.1017/s0007114508094671 19079950 | Outcome
233 | Lignell, S, Winkvist, A, Bertz, F, Rasmussen, KM, Glynn, A, Aune, M, Brekke, HK. Environmental organic pollutants in human milk before and after weight loss. Chemosphere. 2016. 159:96–102. doi:10.1016/j.chemosphere.2016.05.077 27281542 | Intervention/Exposure; Outcome
234 | Lima, ACD, Cecatti, C, Fidélix, MP, Adorno, MAT, Sakamoto, IK, Cesar, TB, Sivieri, K. Effect of Daily Consumption of Orange Juice on the Levels of Blood Glucose, Lipids, and Gut Microbiota Metabolites: Controlled Clinical Trials. Journal of Medicinal Food. 2019. 22:202–210. doi:10.1089/jmf.2018.0080.30638420 | Study design
235 | Linderborg, KM, Kalpio, M, Makela, J, Niinikoski, H, Kallio, HP, Lagstrom, H. Tandem mass spectrometric analysis of human milk triacylglycerols from normal weight and overweight mothers on different diets. Food Chem. 2014. 146:583–90. doi:10.1016/j.foodchem.2013.09.092 24176384 | Intervention/Exposure; Outcome
236 | Liu, M, Chen, QT, Li, ZC, Zhang, J, Wang, PG, He, QQ. Association Between Diet Quality and Cardiometabolic Risk Factor Clustering Stratified by Socioeconomic Status Among Chinese Children. J Acad Nutr Diet. 2021. 121:1975–1983.e2. doi:10.1016/j.jand.2021.03.009.33893062 | Int/Exp: Not relevant; Outcome
237 | Liu, X, Wang, X, Tian, Y, Yang, Z, Lin, L, Lin, Q, Zhang, Z, Li, L. Reduced maternal calcium intake through nutrition and supplementation is associated with adverse conditions for both the women and their infants in a Chinese population. Medicine (Baltimore). 2017. 96:e6609. doi:10.1097/md.0000000000006609 28471956 | Outcome; Country
238 | Liu, X, Wang, X, Tian, Y, Yang, Z, Lin, L, Lin, Q, Zhang, Z, Li, L. Reduced maternal calcium intake through nutrition and supplementation is associated with adverse conditions for both the women and their infants in a Chinese population. Medicine (Baltimore). 2017. 96:e6609. doi:10.1097/md.0000000000006609 28471956 | Comparator; Outcome
239 | Liu, Z, Li, Q, Maddison, R, Ni Mhurchu, C, Jiang, Y, Wei, DM, Cheng, L, Cheng, Y, Wang, D, Wang, HJ. A School-Based Comprehensive Intervention for Childhood Obesity in China: A Cluster Randomized Controlled Trial. Childhood obesity (Print). 2019. 15:105–115. doi:10.1089/chi.2018.0251.30565955 | Int/Exp: Not relevant
240 | Lommi, S, Engberg, E, Tuorila, H, Kolho, KL, Viljakainen, H. Sex- and weight-specific changes in the frequency of sweet treat consumption during early adolescence: a longitudinal study. Br J Nutr. 2021. 126:1592–1600. doi:10.1017/s0007114521001112.33787473 | Comparator; Outcome
241 | Lovelady, CA, Stephenson, KG, Kuppler, KM, Williams, JP. The effects of dieting on food and nutrient intake of lactating women. J Am Diet Assoc. 2006. 106:908–12. doi:10.1016/j.jada.2006.03.007 16720131 | Intervention/Exposure; Outcome
242 | Lovelady, CA, Williams, JP, Garner, KE, Moreno, KL, Taylor, ML, Leklem, JE. Effect of energy restriction and exercise on vitamin B-6 status of women during lactation. Med Sci Sports Exerc. 2001. 33:512–8. doi:10.1097/00005768-200104000-00002 11283424 | Intervention/Exposure
243 | Lovell, AL, Milne, T, Matsuyama, M, Hill, RJ, Davies, PSW, Grant, CC, Wall, CR. Protein Intake, IGF-1 Concentrations, and Growth in the Second Year of Life in Children Receiving Growing Up Milk - Lite (GUMLi) or Cow's Milk (CM) Intervention. Front Nutr. 2021. 8:666228. doi:10.3389/fnut.2021.666228.34179057 | Population at Intervention/exposure
244 | Lowndes, J, Sinnett, SS, Rippe, JM. No Effect of Added Sugar Consumed at Median American Intake Level on Glucose Tolerance or Insulin Resistance. Nutrients. 2015. 7:8830–45. doi:10.3390/nu7105430 26512691 | Comparator
245 | Lu, JH, He, JR, Shen, SY, Wei, XL, Chen, NN, Yuan, MY, Qiu, L, Li, WD, Chen, QZ, Hu, CY, Xia, HM, Bartington, S, Cheng, KK, Lam, KBH, Qiu, X. Does tea consumption during early pregnancy have an adverse effect on birth outcomes?. Birth. 2017. 44:281–289. doi:10.1111/birt.12285 28321896 | Outcome
246 | Ludvigsson, JF, Ludvigsson, J. Milk consumption during pregnancy and infant birthweight. Acta Paediatr. 2004. 93:1474–8. doi:10.1080/08035250410018319 15513575 | Outcome; Population
247 | Ludvigsson, JF, Ludvigsson, J. Milk consumption during pregnancy and infant birthweight. Acta Paediatr. 2004. 93:1474–8. doi:10.1080/08035250410018319 15513575 | Outcome
248 | Ludwig, DS. Artificially sweetened beverages: cause for concern. Jama. 2009. 302:2477–8. doi:10.1001/jama.2009.1822 19996404 | Study design
249 | Lundeen, E, Park, S, Baidal, JAW, Sharma, A, Blanck, HM. Prevalence of and Factors Associated with Sugar-sweetened Beverage Intake Among Women of Reproductive Age-12 States and District of Columbia, 2017 (P16–022-19). Curr Dev Nutr. 2019. 3:1414. doi:10.1093/cdn/nzz050.P16-022-19 | Pub status
250 | Luoto, R, Laitinen, K, Nermes, M, Isolauri, E. Impact of maternal probiotic-supplemented dietary counseling during pregnancy on colostrum adiponectin concentration: a prospective, randomized, placebo-controlled study. Early Hum Dev. 2012. 88:339–44. doi:10.1016/j.earlhumdev.2011.09.006 21945174 | Intervention/Exposure
251 | Lyu JL, Liu Z, Zhou S, Feng XX, Lin Y, Gao AY, Zhang F, Li L, Hebestreit A, Wang HJ. The Effect of a Multifaceted Intervention on Dietary Quality in Schoolchildren and the Mediating Effect of Dietary Quality between Intervention and Changes in Adiposity Indicators: A Cluster Randomized Controlled Trial. Nutrients. 2022;14(16):3272. doi:10.3390/nu14163272 36014777 | Int/Exp: Not relevant
252 | Mahdavi, R, Nikniaz, L, Arefhosseini, S. Energy, fluids intake and beverages consumption pattern among lactating women in Tabriz, Iran. Pakistan Journal of Nutrition. 2009. 8:69–73. doi:10.3923/pjn.2009.69.73 | Outcome; Population
253 | Maillot, M, Vieux, F, Rehm, CD, Rose, CM, Drewnowski, A. Consumption Patterns of Milk and 100% Juice in Relation to Diet Quality and Body Weight Among United States Children: Analyses of NHANES 2011–16 Data. Front Nutr. 2019. 6:117. doi:10.3389/fnut.2019.00117.31440512 | Study design
254 | Maitland, R, Patel, N, Barr, S, Sherry, C, Marriage, B, Seed, P, Garcia Fernandez, L, Lopez Pedrosa, JM, Murphy, H, Rueda, R, Poston, L. A Slow-Digesting, Low-Glycemic Load Nutritional Beverage Improves Glucose Tolerance in Obese Pregnant Women Without Gestational Diabetes. Diabetes Technol Ther. 2018. 20:672–680. doi:10.1089/dia.2018.0102 30204483 | Intervention/Exposure; Outcome
255 | Mallett, LJ, Premkumar, V, Brown, LJ, May, J, Rollo, ME, Schumacher, TL. Total water intake by kilogram of body weight: Analysis of the Australian 2011 to 2013 National Nutrition and Physical Activity Survey. Nutr Diet. 2021. 78:496–505. doi:10.1111/1747-0080.12697.34327801 | Study design
256 | Mangano, KM, Sahni, S, Kiel, DP, Tucker, KL, Dufour, AB, Hannan, MT. Dietary protein is associated with musculoskeletal health independently of dietary pattern: the Framingham Third Generation Study. Am J Clin Nutr. 2017. 105:714–722. doi:10.3945/ajcn.116.136762 28179224 | Intervention/exposure; Outcome
257 | Manios, Y, Lambrinou, CP, Mavrogianni, C, Cardon, G, Lindström, J, Iotova, V, Tankova, T, Rurik, I, Stappen, VV, Kivelä, J, Mateo-Gallego, R, Moreno, LΑ, Makrilakis, K, Androutsos, O. Lifestyle Changes Observed among Adults Participating in a Family- and Community-Based Intervention for Diabetes Prevention in Europe: The 1(st) Year Results of the Feel4Diabetes-Study. Nutrients. 2020. 12(7):1949. doi:10.3390/nu12071949.32629949 | Int/Exp: Not relevant; Outcome
258 | Mannion, CA, Gray-Donald, K, Johnson-Down, L, Koski, KG. Lactating women restricting milk are low on select nutrients. J Am Coll Nutr. 2007. 26:149–55. doi:10.1080/07315724.2007.10719596 17536126 | Outcome
259 | Mardones, F, Urrutia, MT, Villarroel, L, Rioseco, A, Castillo, O, Rozowski, J, Tapia, JL, Bastias, G, Bacallao, J, Rojas, I. Effects of a dairy product fortified with multiple micronutrients and omega-3 fatty acids on birth weight and gestation duration in pregnant Chilean women. Public Health Nutr. 2008. 11:30–40. doi:10.1017/s1368980007000110 17565762 | Intervention/Exposure; Comparator
260 | Marshall, TA, Curtis, AM, Cavanaugh, JE, Warren, JJ, Levy, SM. Child and Adolescent Sugar-Sweetened Beverage Intakes Are Longitudinally Associated with Higher Body Mass Index z Scores in a Birth Cohort Followed 17 Years. Journal of the Academy of Nutrition and Dietetics. 2019. 119:425–434. doi:10.1016/j.jand.2018.11.003.30638821 | Duplicate
261 | Martin, CL, Siega-Riz, AM, Sotres-Alvarez, D, Robinson, WR, Daniels, JL, Perrin, EM, Stuebe, AM. Maternal Dietary Patterns are Associated with Lower Levels of Cardiometabolic Markers during Pregnancy. Paediatr Perinat Epidemiol. 2016. 30:246–55. doi:10.1111/ppe.12279 26848932 | Intervention/Exposure; Outcome
262 | Martin, KR, Coles, KM. Consumption of 100% tart cherry juice reduces serum urate in overweight and obese adults. Current Developments in Nutrition. 2019. 3(5):nzz011. doi:10.1093/cdn/nzz011.31037275 | Outcome
263 | Martínez-López, S, Sarriá, B, Mateos, R, Bravo-Clemente, L. Moderate consumption of a soluble green/roasted coffee rich in caffeoylquinic acids reduces cardiovascular risk markers: results from a randomized, cross-over, controlled trial in healthy and hypercholesterolemic subjects. Eur J Nutr. 2019. 58:865–878. doi:10.1007/s00394-018-1726-x 29858625 | Duplicate; Other; Included in 2020 DGs
264 | Martini, D, Rosi, A, Tassotti, M, Antonini, M, Dall'Asta, M, Bresciani, L, Fantuzzi, F, Spigoni, V, Domínguez-Perles, R, Angelino, D, Ricci, C, Del Pozo-Luengo, S, Tornel, PL, Scazzina, F, Gil-Izquierdo, A, Dei Cas, A, Brighenti, F, Bonadonna, R, Del Rio, D, Mena, P. Effect of coffee and cocoa-based confectionery containing coffee on markers of cardiometabolic health: results from the pocket-4-life project. Eur J Nutr. 2021. 60:1453–1463. doi:10.1007/s00394-02002347-5.32728879 | EXCLUDE
265 | Martucci, M, Conte, M, Bucci, L, Giampieri, E, Fabbri, C, Palmas, MG, Izzi, M, Salvioli, S, Zambrini, AV, Orsi, C, Brigidi, P, Santoro, A, Capri, M, Monti, D, Franceschi, C. Twelve-week daily consumption of Ad Hoc fortified milk with ω-3, D, and group B vitamins has a positive impact on inflammaging parameters: A randomized cross-over trial. Nutrients. 2020. 12:1–19. doi:10.3390/nu12113580. | Comparator; Outcome
266 | Maskarinec, G, Jacobs, S, Shvetsov, Y, Boushey, CJ, Setiawan, VW, Kolonel, LN, Haiman, CA, Le Marchand, L. Intake of cocoa products and risk of type-2 diabetes: the multiethnic cohort. Eur J Clin Nutr. 2019. 73:671–678. doi:10.1038/s41430-018-0188-9 29795238 | Intervention/exposure; Outcome
267 | Matthews, J, Torres, SJ, Milte, CM, Hopkins, I, Kukuljan, S, Nowson, CA, Daly, RM. Effects of a multicomponent exercise program combined with calcium-vitamin D(3)-enriched milk on health-related quality of life and depressive symptoms in older men: secondary analysis of a randomized controlled trial. Eur J Nutr. 2020. 59:1081–1091. doi:10.1007/s00394-019-01969-8 30993400 | Intervention/exposure
268 | Matthews, J, Torres, SJ, Milte, CM, Hopkins, I, Kukuljan, S, Nowson, CA, Daly, RM. Effects of a multicomponent exercise program combined with calcium–vitamin D3-enriched milk on health-related quality of life and depressive symptoms in older men: secondary analysis of a randomized controlled trial. European Journal of Nutrition. 2020. 59:1081–1091. doi:10.1007/s00394-019-01969-8.30993400 | Int/Exp: Not relevant
269 | Mazurkiewicz, D, Bronkowska, M. Circulating Insulin and IGF-1 and Frequency of Food Consumption during Pregnancy as Predictors of Birth Weight and Length. Nutrients. 2021. 13(7):2344. doi:10.3390/nu13072344.34371854 | Study design
270 | McCormick, DP, Reyna, L, Reifsnider, E. Calories, Caffeine and the Onset of Obesity in Young Children. Acad Pediatr. 2020. 20:801–808. doi:10.1016/j.acap.2020.02.014.32081767 | Int/Exp: Not relevant; Population at Intervention/exposure
271 | McElfish, PearlA, Felix, HollyC, Bursac, Zoran, Rowland, Brett, Yeary, KarenHK, Long, ChristopherR, Selig, JamesP, Joseph Keawe'aimoku Kaholokula, , Riklon, Sheldon. A Cluster Randomized Controlled Trial Comparing Diabetes Prevention Program Interventions for Overweight/Obese Marshallese Adults. Inquiry (00469580). 2023. 60:1–14. doi:10.1177/00469580231152051. | Int/Exp: Not relevant
272 | McGovern, Caitriona, Rifas-Shiman, SherylL, Switkowski, KarenM, Woo Baidal, JenniferA, Lightdale, JeniferR, Hivert, Marie-France, Oken, Emily, Aris, IzzuddinM. Association of cow's milk intake in early childhood with adiposity and cardiometabolic risk in early adolescence. American Journal of Clinical Nutrition. 2022. 116:561–571. doi:10.1093/ajcn/nqac103.35441227 | Duplicate
273 | McGovern, Caitriona, Rifas-Shiman, SherylL, Switkowski, KarenM, Woo Baidal, JenniferA, Lightdale, JeniferR, Hivert, Marie-France, Oken, Emily, Aris, IzzuddinM. Association of cow's milk intake in early childhood with adiposity and cardiometabolic risk in early adolescence. American Journal of Clinical Nutrition. 2022. 116:561–571. doi:10.1093/ajcn/nqac103.35441227 | Other; Duplicate
274 | Meinila, J, Valkama, A, Koivusalo, SB, Stach-Lempinen, B, Rono, K, Lindstrom, J, Kautiainen, H, Eriksson, JG, Erkkola, M. Is improvement in the Healthy Food Intake Index (HFII) related to a lower risk for gestational diabetes?. Br J Nutr. 2017. 117:1103–1109. doi:10.1017/s0007114517001015 28535829 | Outcome
275 | Mela, DJ. Novel food technologies: enhancing appetite control in liquid meal replacers. Obesity (Silver Spring). 2006. 14 Suppl 4:179s–181s. doi:10.1038/oby.2006.302 16931503 | Study design; Intervention/exposure
276 | Mikkelsen, TB, Osier, M, Orozova-Bekkevold, I, Knudsen, VK, Olsen, SF. Association between fruit and vegetable consumption and birth weight: a prospective study among 43,585 Danish women. Scand J Public Health. 2006. 34:616–22. doi:10.1080/14034940600717688 17132595 | Intervention/Exposure; Outcome
277 | Mirmiran, P, Moslehi, N, Hosseinpanah, F, Sarbazi, N, Azizi, F. Dietary determinants of unhealthy metabolic phenotype in normal weight and overweight/obese adults: results of a prospective study. Int J Food Sci Nutr. 2020. 71:891 –901. doi:10.1080/09637486.2020.1746955.32237941 | Outcome
278 | Misra, A, Ray, S, Patrikar, S. A longitudinal study to determine association of various maternal factors with neonatal birth weight at a tertiary care hospital. Med J Armed Forces India. 2015. 71:270–3. doi: 10.1016/j.mjafi.2015.03.001 26288495 | Population; Country
279 | Miyake, Y, Tanaka, K, Okubo, H, Sasaki, S, Arakawa, M. Maternal caffeine intake in pregnancy is inversely related to childhood peer problems in Japan: The Kyushu Okinawa Maternal and Child Health Study. Nutr Neurosci. 2018. 22(11):1–8. doi:10.1080/1028415X.2018.1450089 | Intervention/Exposure; Outcome
280 | Miyake, Y, Tanaka, K, Okubo, H, Sasaki, S, Arakawa, M. Maternal caffeine intake in pregnancy is inversely related to childhood peer problems in Japan: The Kyushu Okinawa Maternal and Child Health Study. Nutr Neurosci. 2019. 22:817–824. doi:10.1080/1028415X.2018.1450089 29534651 | Intervention/exposure; Outcome; Population at Intervention/exposure
281 | Miyake, Y, Tanaka, K, Okubo, H, Sasaki, S, Furukawa, S, Arakawa, M. Milk intake during pregnancy is inversely associated with the risk of postpartum depressive symptoms in Japan: the Kyushu Okinawa Maternal and Child Health Study. Nutr Res. 2016. 36:907–913. doi: 10.1016/j.nutres.2016.06.001 27632910 | Outcome
282 | Modzelewska, D, Bellocco, R, Elfvin, A, Brantsaeter, AL, Meltzer, HM, Jacobsson, B, Sengpiel, V. Caffeine exposure during pregnancy, small for gestational age birth and neonatal outcome - results from the Norwegian Mother and Child Cohort Study. BMC Pregnancy Childbirth. 2019. 19:80. doi:10.1186/s12884-019-2215-9 30808339 | Outcome
283 | Montenegro-Bethancourt, G, Johner, SA, Remer, T. Contribution of fruit and vegetable intake to hydration status in schoolchildren. Am J Clin Nutr. 2013. 98:1103–12. doi:10.3945/ajcn.112.051490 23966431 | Outcome
284 | Moran Lev, H, Cohen, S, Lubetzky, R. Coffee and tea consumption in relation with weight control-a randomized clinical trial. Journal of pediatric gastroenterology and nutrition. 2022. 74:1120–1121. doi:10.1097/MPG.0000000000003446. | Publication status
285 | Moran, LJ, Sui, Z, Cramp, CS, Dodd, JM. A decrease in diet quality occurs during pregnancy in overweight and obese women which is maintained post-partum. Int J Obes (Lond). 2013. 37:704–11. doi: 10.1038/ijo.2012.129 22868828 | Intervention/Exposure; Outcome
286 | Moura de Araujo MF, Gueiros Gaspar MW, Saraiva Veras V, Freire de Freitas RWJ, de Paula MDL, Alves de Oliveira Serra MA, Garcia Lira Neto JC, Coelho Damasceno MM, Bandeira Moreira AV, Derenji de Mello V. Consumption of caffeinated and decaffeinated coffee enriched with cocoa and fructo-oligosaccharides among non-diabetic persons: Double blind randomized clinical trial. J Food Biochem. 2022;46(5):e14081. doi: 10.1111/jfbc.14081.35064574 | Int/Exp: Not relevant
287 | Moura de Araujo, MF, Gueiros Gaspar, MW, Saraiva Veras, V, Freire de Freitas, RWJ, de Paula, MDL, Alves de Oliveira Serra, MA, Garcia Lira Neto, JC, Coelho Damasceno, MM, Bandeira Moreira, AV, Derenji de Mello, V. Consumption of caffeinated and decaffeinated coffee enriched with cocoa and fructo-oligosaccharides among non-diabetic persons: double blind randomized clinical trial. Journal of food biochemistry. 2022. 46(5):e14081-. doi:10.1111/jfbc.14081.35064574 | Duplicate; Other; Duplicate of Ref 13110
288 | Moura de Araujo, MF, Gueiros Gaspar, MW, Saraiva Veras, V, Freire de Freitas, RWJ, de Paula, MDL, Alves de Oliveira Serra, MA, Garcia Lira Neto, JC, Coelho Damasceno, MM, Bandeira Moreira, AV, Derenji de Mello, V. Consumption of caffeinated and decaffeinated coffee enriched with cocoa and fructo-oligosaccharides among non-diabetic persons: double blind randomized clinical trial. Journal of food biochemistry. 2022. 46(5):e14081-. doi:10.1111/jfbc.14081.35064574 | Other; Duplicate
289 | Mparmpakas, D, Goumenou, A, Zachariades, E, Pados, G, Gidron, Y, Karteris, E. Immune system function, stress, exercise and nutrition profile can affect pregnancy outcome: Lessons from a Mediterranean cohort. Exp Ther Med. 2013. 5:411–418. doi:10.3892/etm.2012.849 23404257 | Outcome
290 | Mrdjenovic, G, Levitsky, DA. Nutritional and energetic consequences of sweetened drink consumption in 6- to 13-year-old children. J Pediatr. 2003. 142:604–10. doi:10.1067/mpd.2003.200 12838186 | Duplicate; Other; Included in 2020 DGs
291 | Mukhopadhyay, A, Dwarkanath, P, Bhanji, S, Devi, S, Thomas, A, Kurpad, AV, Thomas, T. Maternal intake of milk and milk proteins is positively associated with birth weight: A prospective observational cohort study. Clin Nutr ESPEN. 2018. 25:103–109. doi: 10.1016/j.clnesp.2018.03.125 29779803 | Outcome; Country
292 | Murrin, CM, Heinen, MM, Kelleher, CC. Are Dietary Patterns of Mothers during Pregnancy Related to Children's Weight Status? Evidence from the Lifeways Cross- Generational Cohort Study. AIMS Public Health. 2015. 2:274–296. doi:10.3934/publichealth.2015.3.274 29546111 | Population
293 | Nagata, C, Takatsuka, N, Shimizu, H, Hayashi, H, Akamatsu, T, Murase, K. Effect of soymilk consumption on serum estrogen and androgen concentrations in Japanese men. Cancer Epidemiol Biomarkers Prev. 2001. 10:179–84.11303585 | Outcome; Other; no between group statistical comparison for weight
294 | Najar Sedgh Doust, F, Sharifan, P, Razmi, M, Sadat ekhteraei Toussi, M, Taghizadeh, N, Yaghooti-Khorasani, M, Mohammadi Bajgiran, M, Ghazizadeh, H, Darroudi, S, Esmaily, H, Akbari, N, Rastegar Moghadam, N, Khedmatgozar, H, Ferns, G, Assaran darban, R, Ghayour-Mobarhan, M. Effects of vitamin D3-fortified low-fat yogurt and milk on serum cytokine levels and anti hsp-27 antibody titer in adults with abdominal obesity: A randomized clinical trial. Obesity Medicine. 2022. 30:100382. doi:10.1016/j.obmed.2021.100382 | Int/Exp: Not relevant; Comparator
295 | Nakagi, Y, Ito, T, Hirooka, K, Sugioka, Y, Endo, H, Saijo, Y, Imai, H, Takeda, H, Kayama, F, Sasaki, S, Yoshida, T. Association between lifestyle habits and bone mineral density in Japanese juveniles. Environ Health Prev Med. 2010. 15:222–8. doi:10.1007/s12199-009-01318 21432549 | Intervention/exposure; Outcome
296 | Ochiai, R, Chikama, A, Kataoka, K, Tokimitsu, I, Maekawa, Y, Ohishi, M, Rakugi, H, Mikami, H. Effects of hydroxyhydroquinone-reduced coffee on vasoreactivity and blood pressure. Hypertens Res. 2009. 32:969–74. doi:10.1038/hr.2009.132 19713967 | Intervention/exposure
297 | O'Connor, LM, Lentjes, MA, Luben, RN, Khaw, KT, Wareham, NJ, Forouhi, NG. Dietary dairy product intake and incident type 2 diabetes: a prospective study using dietary data from a 7-day food diary. Diabetologia. 2014. 57:909–17. doi: 10.1007/s00125-014-3176-1 24510203 | Outcome
298 | O'Connor, S, Julien, P, Weisnagel, SJ, Gagnon, C, Rudkowska, I. Impact of a High Intake of Dairy Product on Insulin Sensitivity in Hyperinsulinemic Adults: A Crossover Randomized Controlled Trial. Curr Dev Nutr. 2019. 3:nzz083. doi:10.1093/cdn/nzz083.31453424 | Int/Exp: Not relevant
299 | Oken, E, Ning, Y, Rifas-Shiman, SL, Rich-Edwards, JW, Olsen, SF, Gillman, MW. Diet during pregnancy and risk of preeclampsia or gestational hypertension. Ann Epidemiol. 2007. 17:663–8. doi: 10.1016/j.annepidem.2007.03.003 17521921 | Outcome
300 | Okop, KJ, Lambert, EV, Alaba, O, Levitt, NS, Luke, A, Dugas, L, Rvh, D, Kroff, J, Micklesfield, LK, Kolbe-Alexander, TL, Warren, S, Dugmore, H, Bobrow, K, OdunitanWayas, FA, Puoane, T. Sugar-sweetened beverage intake and relative weight gain among South African adults living in resource-poor communities: longitudinal data from the STOP-SA study. International Journal of Obesity. 2019. 43:603–614. doi: 10.1038/s41366-018-0216-9.30283079 | Country
301 | Okubo, H, Miyake, Y, Sasaki, S, Tanaka, K, Murakami, K, Hirota, Y, Kanzaki, H, Kitada, M, Horikoshi, Y, Ishiko, O, Nakai, Y, Nishio, J, Yamamasu, S, Yasuda, J, Kawai, S, Yanagihara, K, Wakuda, K, Kawashima, T, Narimoto, K, Iwasa, Y, Orino, K, Tsunetoh, I, Yoshida, J, Iito, J, Kaneko, T, Kamiya, T, Kuribayashi, H, Taniguchi, T, Takemura, H, Morimoto, Y, Matsunaga, I, Oda, H, Ohya, Y. Maternal dietary patterns in pregnancy and fetal growth in Japan: the Osaka Maternal and Child Health Study. Br J Nutr. 2012. 107:1526–33. doi:10.1017/s0007114511004636 21929833 | Outcome; Population
302 | Okubo, H, Miyake, Y, Tanaka, K, Sasaki, S, Hirota, Y. Maternal total caffeine intake, mainly from Japanese and Chinese tea, during pregnancy was associated with risk of preterm birth: the Osaka Maternal and Child Health Study. Nutr Res. 2015. 35:309–16. doi:10.1016/j.nutres.2015.02.009 25773355 | Outcome; Population
303 | Olmedo-Requena, R, Amezcua-Prieto, C, Luna-Del-Castillo Jde, D, Lewis-Mikhael, AM, Mozas-Moreno, J, Bueno-Cavanillas, A, Jimenez-Moleon, JJ. Association Between Low Dairy Intake During Pregnancy and Risk of Small-for-Gestational-Age Infants. Matern Child Health J. 2016. 20:1296–304. doi:10.1007/s10995-016-1931-2 26971269 | Outcome; Population
304 | Olsen, SF, Halldorsson, TI, Willett, WC, Knudsen, VK, Gillman, MW, Mikkelsen, TB, Olsen, J. Milk consumption during pregnancy is associated with increased infant size at birth: prospective cohort study. Am J Clin Nutr. 2007. 86:1104–10. doi:10.1093/ajcn/86.4.1104 17921389 | Intervention/Exposure
305 | Otsuka R, Zhang S, Tange C, Association of Dietary Intake with the Transitions of Frailty among JapaneseCommunity-Dwelling Older Adults. J Frailty Aging. 2022;11(1):26–32. doi:10.14283/jfa.2021.42 35122087 | Outcome
306 | Ottestad, I, Løvstad, AT, Gjevestad, GO, Hamarsland, H, Šaltytė Benth, J, Andersen, LF, Bye, A, Biong, AS, Retterstøl, K, Iversen, PO, Raastad, T, Ulven, SM, Holven, KB. Intake of a Protein-Enriched Milk and Effects on Muscle Mass and Strength. A 12-Week Randomized Placebo Controlled Trial among Community-Dwelling Older Adults. J Nutr Health Aging. 2017. 21:1160–1169. doi:10.1007/s12603-016-0856-1 29188875 | Comparator
307 | Palmer, MS, Logan, HM, Spriet, LL. On-ice sweat rate, voluntary fluid intake, and sodium balance during practice in male junior ice hockey players drinking water or a carbohydrate-electrolyte solution. Appl Physiol Nutr Metab. 2010. 35:328–35. doi:10.1139/h10-027 20555377 | Intervention/exposure; EXCLUDE
308 | Papadopoulou, E, Botton, J, Brantsæter, AL, Haugen, M, Alexander, J, Meltzer, HM, Bacelis, J, Elfvin, A, Jacobsson, B, Sengpiel, V. Maternal caffeine intake during pregnancy and childhood growth and overweight: Results from a large Norwegian prospective observational cohort study. BMJ Open. 2018. 8:e018895. doi:10.1136/bmjopen-2017-018895 | Intervention/Exposure; Population
309 | Papageorgiou AL, Efthymiou V, Giannouli A, Xekouki P, Kranioti CC, Chrousos GP. Comparison of Hospital Consultation and Summer Camp Lifestyle Intervention Programs for Sustained Body Weight Loss in Overweight/Obese Greek Children. Children (Basel). 2022;9(1):86. Published 2022 Jan 8. doi:10.3390/children9010086.35053711 | Int/Exp: Not relevant
310 | Papageorgiou, AnnaL, Efthymiou, Vasiliki, Giannouli, Aikaterini, Xekouki, Paraskevi, Kranioti, ChristinaC, Chrousos, GeorgeP. Comparison of Hospital Consultation and Summer Camp Lifestyle Intervention Programs for Sustained Body Weight Loss in Overweight/Obese Greek Children. Children. 2022. 9:86–86. doi:10.3390/children9010086.35053711 | Int/Exp: Not relevant
311 | Parazzini, F, Chiaffarino, F, Chatenoud, L, Tozzi, L, Cipriani, S, Chiantera, V, Fedele, L. Maternal coffee drinking in pregnancy and risk of small for gestational age birth. Eur J Clin Nutr. 2005. 59:299–301. doi:10.1038/sj.ejcn.1602052 15454971 | Outcome
312 | Parvez, S, Gerona, RR, Proctor, C, Friesen, M, Ashby, JL, Reiter, JL, Lui, Z, Winchester, PD. Glyphosate exposure in pregnancy and shortened gestational length: A prospective Indiana birth cohort study. Environmental Health: A Global Access Science Source. 2018. 17(1):23. doi:10.1186/s12940-018-0367-0 29519238 | Intervention/Exposure
313 | Patelarou, E, Kargaki, S, Stephanou, EG, Nieuwenhuijsen, M, Sourtzi, P, Gracia, E, Chatzi, L, Koutis, A, Kogevinas, M. Exposure to brominated trihalomethanes in drinking water and reproductive outcomes. Occup Environ Med. 2011. 68:438–45. doi:10.1136/oem.2010.056150 20952554 | Outcome; Population
314 | Peacock, A, Hutchinson, D, Wilson, J, McCormack, C, Bruno, R, Olsson, CA, Allsop, S, Elliott, E, Burns, L, Mattick, RP. Adherence to the Caffeine Intake Guideline during Pregnancy and Birth Outcomes: A Prospective Cohort Study. Nutrients. 2018. 10(3):319. doi:10.3390/nu10030319 29518946 | Outcome
315 | Pereira, MA, Parker, ED, Folsom, AR. Coffee consumption and risk of type 2 diabetes mellitus: an 11-year prospective study of 28 812 postmenopausal women. Arch Intern Med. 2006. 166:1311–6. doi:10.1001/archinte.166.12.1311 16801515 | Outcome
316 | Pereira, S, Katzmarzyk, PT, Hedeker, D, Maia, J. Change and Stability in Sibling Resemblance in Obesity Markers: The Portuguese Sibling Study on Growth, Fitness, Lifestyle, and Health. J Obes. 2019. 2019:2432131. doi:10.1155/2019/2432131.31827922 | Int/Exp: Not relevant
317 | Perez-Ferre, N, Fernandez, D, Torrejon, MJ, Del Prado, N, Runkle, I, Rubio, MA, Montanez, C, Bordiu, E, Calle-Pascual, A. Effect of lifestyle on the risk of gestational diabetes and obstetric outcomes in immigrant Hispanic women living in Spain. J Diabetes. 2012. 4:432–8. doi:10.1111/j.1753-0407.2012.00221.x 22742428 | Intervention/Exposure
318 | Perng, W, Tang, L, Song, PXK, Goran, M, Tellez Rojo, MM, Cantoral, A, Peterson, KE. Urate and Nonanoate Mark the Relationship between Sugar-Sweetened Beverage Intake and Blood Pressure in Adolescent Girls: A Metabolomics Analysis in the ELEMENT Cohort. Metabolites. 2019. 9(5):100. doi:10.3390/metabo9050100 31108933 | Study design
319 | Petherick, ES, Goran, MI, Wright, J. Relationship between artificially sweetened and sugar-sweetened cola beverage consumption during pregnancy and preterm delivery in a multi-ethnic cohort: Analysis of the Born in Bradford cohort study. European Journal of Clinical Nutrition. 2014. 68:404–407. doi:10.1038/ejcn.2013.267 24398641 | Outcome
320 | Petrova, D, Bernabeu Litrán, MA, García-Mármol, E, Rodríguez-Rodríguez, M, Cueto-Martín, B, López-Huertas, E, Catena, A, Fonollá, J. Еffects of fortified milk on cognitive abilities in school-aged children: results from a randomized-controlled trial. Eur J Nutr. 2019. 58:1863–1872. doi:10.1007/s00394-018-1734-x. | Comparator
321 | Petrova, D, Bernabeu Litrán, MA, García-Mármol, E, Rodríguez-Rodríguez, M, Cueto-Martín, B, López-Huertas, E, Catena, A, Fonollá, J. Еffects of fortified milk on cognitive abilities in school-aged children: results from a randomized-controlled trial. Eur J Nutr. 2019. 58:1863–1872. doi:10.1007/s00394-018-1734-x | Intervention/exposure; Comparator
322 | Phelan, S, Abrams, B, Wing, RR. Prenatal Intervention with Partial Meal Replacement Improves Micronutrient Intake of Pregnant Women with Obesity. Nutrients. 2019. 11(5):1071. doi:10.3390/nu11051071 31091748 | Intervention/Exposure
323 | Phelan, S, Hagobian, TA, Ventura, A, Brannen, A, Erickson-Hatley, K, Schaffner, A, Munoz-Christian, K, Mercado, A, Tate, DF. 'Ripple' effect on infant zBMI trajectory of an internet-based weight loss program for low-income postpartum women. Pediatr Obes. 2019. 14(1):e12546. doi:10.1111/ijpo.12456 | Outcome
324 | Phelan, S, Hart, C, Phipps, M, Abrams, B, Schaffner, A, Adams, A, Wing, R. Maternal behaviors during pregnancy impact offspring obesity risk. Exp Diabetes Res. 2011. 2011:985139. doi:10.1155/2011/985139 22110475 | Outcome; Population
325 | Phelan, S, Wing, RR, Brannen, A, McHugh, A, Hagobian, T, Schaffner, A, Jelalian, E, Hart, CN, Scholl, TO, Munoz-Christian, K, , . Does Partial Meal Replacement During Pregnancy Reduce 12-Month Postpartum Weight Retention?. Obesity (silver spring, md.). 2018. 27(2):226–236. doi:10.1002/oby.22361 30421864 | Intervention/Exposure
326 | Phelan, S, Wing, RR, Brannen, A, McHugh, A, Hagobian, T, Schaffner, A, Jelalian, E, Hart, CN, Scholl, TO, Munoz-Christian, K, Yin, E, Phipps, MG, Keadle, S, Abrams, B. Does Partial Meal Replacement During Pregnancy Reduce 12-Month Postpartum Weight Retention?. Obesity (Silver Spring). 2019. 27:226–236. doi:10.1002/oby.22361 30421864 | Intervention/Exposure
327 | Phelan, S, Wing, RR, Brannen, A, McHugh, A, Hagobian, TA, Schaffner, A, Jelalian, E, Hart, CN, Scholl, TO, Munoz-Christian, K, Yin, E, Phipps, MG, Keadle, S, Abrams, B. Randomized controlled clinical trial of behavioral lifestyle intervention with partial meal replacement to reduce excessive gestational weight gain. Am J Clin Nutr. 2018. 107:183–194. doi:10.1093/ajcn/nqx043 29529157 | Intervention/Exposure
328 | Pinto, TJ, Farias, DR, Rebelo, F, Lepsch, J, Vaz, JS, Moreira, JD, Cunha, GM, Kac, G. Lower inter-partum interval and unhealthy life-style factors are inversely associated with n-3 essential fatty acids changes during pregnancy: a prospective cohort with Brazilian women. PLoS One. 2015. 10:e0121151. doi:10.1371/journal.pone.0121151 25822204 | Intervention/Exposure; Outcome
329 | Pollak, KI, Alexander, SC, Bennett, G, Lyna, P, Coffman, CJ, Bilheimer, A, Farrell, D, Bodner, ME, Swamy, GK, Ostbye, T. Weight-related SMS texts promoting appropriate pregnancy weight gain: a pilot study. Patient Educ Couns. 2014. 97:256–60. doi:10.1016/j.pec.2014.07.030 25153313 | Intervention/Exposure
330 | Ponzo, V, Goitre, I, Fadda, M, Gambino, R, De Francesco, A, Soldati, L, Gentile, L, Magistroni, P, Cassader, M, Bo, S. Dietary flavonoid intake and cardiovascular risk: a population-based cohort study. J Transl Med. 2015. 13:218. doi:10.1186/s12967-015-0573-2 26152229 | Intervention/exposure
331 | Psaltopoulou, T, Naska, A, Orfanos, P, Trichopoulos, D, Mountokalakis, T, Trichopoulou, A. Olive oil, the Mediterranean diet, and arterial blood pressure: the Greek European Prospective Investigation into Cancer and Nutrition (EPIC) study. Am J Clin Nutr. 2004. 80:1012–8. doi:10.1093/ajcn/80.4.1012 15447913 | Intervention/exposure; Outcome
332 | Puma, JE, Thompson, D, Baer, K, Haemer, MA, Gilbert, K, Hambidge, M, Krebs, NF. Enhancing Periconceptional Health by Targeting Postpartum Mothers at Rural WIC Clinics. Health Promot Pract. 2018. 19:390–399. doi:10.1177/1524839917699553 28438036 | Intervention/Exposure
333 | Purdue-Smithe, AC, Manson, JE, Hankinson, SE, Bertone-Johnson, ER. A prospective study of caffeine and coffee intake and premenstrual syndrome. Am J Clin Nutr. 2016. 104:499–507. doi:10.3945/ajcn.115.127027 27385613 | Outcome
334 | Radesky, JS, Oken, E, Rifas-Shiman, SL, Kleinman, KP, Rich-Edwards, JW, Gillman, MW. Diet during early pregnancy and development of gestational diabetes. Paediatr Perinat Epidemiol. 2008. 22:47–59. doi:10.1111/j.1365-3016.2007.00899.x 18173784 | Outcome
335 | Radulescu, A, Killian, M, Kang, Q, Yuan, Q, Softic, S. Dietary Counseling Aimed at Reducing Sugar Intake Yields the Greatest Improvement in Management of Weight and Metabolic Dysfunction in Children with Obesity. Nutrients. 2022. 14(7):1500. doi:10.3390/nu14071500.35406113 | Int/Exp: Not relevant
336 | Rafey, MF, Murphy, CF, Abdalgwad, R, Kilkelly, K, Griffin, H, Beatty, N, O'Shea, PM, Collins, C, McGrath, R, Hynes, M, Davenport, C, O'Donnell, M, Finucane, FM. Effects of a Milk-Based Meal Replacement Program on Weight and Metabolic Characteristics in Adults with Severe Obesity. Diabetes Metab Syndr Obes. 2020. 13:197–205. doi:10.2147/dmso.S226327.32158243 | Study design; Int/exp: Not included bev type; Health Status
337 | Rafey, MF, Murphy, CF, Abdalgwad, R, Kilkelly, K, Griffin, H, Beatty, N, O'Shea, PM, Collins, C, McGrath, R, Hynes, M, Davenport, C, O'Donnell, M, Finucane, FM. Effects of a Milk-Based Meal Replacement Program on Weight and Metabolic Characteristics in Adults with Severe Obesity. Diabetes Metab Syndr Obes. 2020. 13:197–205. doi:10.2147/dmso.S226327.32158243 | Int/Exp: Not relevant
338 | Rahmani, S, Medise, BE, Sjarif, DR. Association between growing-up milk consumption and overweight and obesity in children aged 2–3 years. Journal of Pediatric Gastroenterology & Nutrition. 2022. 74:1128-1128. doi:10.1097/MPG.0000000000003446. | Study design; Country
339 | Rampersaud, GC. 100 % Fruit juice: perspectives amid the sugar debate. Public Health Nutr. 2016. 19:906–13. doi:10.1017/s1368980015001135 25892540 | Study design
340 | Ravn-Haren, G, Dragsted, LO, Buch-Andersen, T, Jensen, EN, Jensen, RI, Németh-Balogh, M, Paulovicsová, B, Bergström, A, Wilcks, A, Licht, TR, Markowski, J, Bügel, S. Intake of whole apples or clear apple juice has contrasting effects on plasma lipids in healthy volunteers. Eur J Nutr. 2013. 52:1875–89. doi:10.1007/s00394-012-0489-z 23271615 | Outcome; EXCLUDE; Other; No statistical test on outomces of interest
341 | Rebholz, CM, Reynolds, K, Wofford, MR, Chen, J, Kelly, TN, Mei, H, Whelton, PK, He, J. Effect of soybean protein on novel cardiovascular disease risk factors: a randomized controlled trial. Eur J Clin Nutr. 2013. 67:58–63. doi:10.1038/ejcn.2012.186 23187956 | Intervention/exposure; Outcome
342 | Reyes-Garcia, R, Garcia-Martin, A, Palacios, S, Salas, N, Mendoza, N, Quesada-Charneco, M, Fonolla, J, Lara-Villoslada, F, Muñoz-Torres, M. Factors Predicting the Response to a Vitamin D-Fortified Milk in Healthy Postmenopausal Women. Nutrients. 2019. 11(11):2641. doi:10.3390/nu11112641.31689902 | Int/Exp: Not relevant
343 | Richter, CK, Skulas-Ray, AC, Gaugler, TL, Meily, S, Petersen, KS, Kris-Etherton, PM. Effects of Cranberry Juice Supplementation on Cardiovascular Disease Risk Factors in Adults with Elevated Blood Pressure: A Randomized Controlled Trial. Nutrients. 2021. 13(8):2618. doi:10.3390/nu13082618.34444779 | Outcome
344 | Rondanelli M, Gasparri C, Perna S, Petrangolini G, Allegrini P, Fazia T, Bernardinelli L, Cavioni A, Mansueto F, Oberto L, Patelli Z, Tartara A, Riva A. A 60-Day Green Tea Extract Supplementation Counteracts the Dysfunction of Adipose Tissue in Overweight Post-Menopausal and Class I Obese Women. Nutrients. 2022;14(24):5209. Published 2022 Dec 7. doi:10.3390/nu14245209.36558368 | Int/Exp: Not relevant
345 | Rosal, MC, Lemon, SC, Borg, A, Lopez-Cepero, A, Sreedhara, M, Silfee, V, Pbert, L, Kane, K, Li, W. The Healthy Kids & Families study: Outcomes of a 24-month childhood obesity prevention intervention. Preventive Medicine Reports. 2023. 31:102086. doi:10.1016/j.pmedr.2022.102086 36820371 | Int/Exp: Not relevant
346 | Ruiz-Gracia, T, Duran, A, Fuentes, M, Rubio, MA, Runkle, I, Carrera, EF, Torrejon, MJ, Bordiu, E, Valle, LD, Garcia de la Torre, N, Bedia, AR, Montanez, C, Familiar, C, Calle-Pascual, AL. Lifestyle patterns in early pregnancy linked to gestational diabetes mellitus diagnoses when using IADPSG criteria. The St Carlos gestational study. Clin Nutr. 2016. 35:699–705. doi:10.1016/j.clnu.2015.04.017 25998584 | Outcome
347 | Salmenhaara, M, Uusitalo, L, Uusitalo, U, Kronberg-Kippila, C, Sinkko, H, Ahonen, S, Veijola, R, Knip, M, Kaila, M, Virtanen, SM. Diet and weight gain characteristics of pregnant women with gestational diabetes. Eur J Clin Nutr. 2010. 64:1433–40. doi:10.1038/ejcn.2010.167 20808329 | Intervention/Exposure; Outcome
348 | Savikin, K, Menković, N, Zdunić, G, Pljevljakušić, D, Spasić, S, Kardum, N, Konić-Ristić, A. Dietary supplementation with polyphenol-rich chokeberry juice improves skin morphology in cellulite. J Med Food. 2014. 17:582–7. doi:10.1089/jmf.2013.0102 24433076 | Study design
349 | Schliep, KC, Schisterman, EF, Mumford, SL, Pollack, AZ, Zhang, C, Ye, A, Stanford, JB, Hammoud, AO, Porucznik, CA, Wactawski-Wende, J. Caffeinated beverage intake and reproductive hormones among premenopausal women in the BioCycle Study. Am J Clin Nutr. 2012. 95:488–97. doi:10.3945/ajcn.111.021287 22237060 | Outcome
350 | Schulz, M, Nöthlings, U, Hoffmann, K, Bergmann, MM, Boeing, H. Identification of a food pattern characterized by high-fiber and low-fat food choices associated with low prospective weight change in the EPIC-Potsdam cohort. J Nutr. 2005. 135:1183–9. doi:10.1093/jn/135.5.1183 15867301 | Intervention/exposure
351 | Scranton, R, Sesso, HD, Stampfer, MJ, Levenson, JW, Buring, JE, Gaziano, JM. Predictors of 14-year changes in the total cholesterol to high-density lipoprotein cholesterol ratio in men. Am Heart J. 2004. 147:1033–8. doi:10.1016/j.ahj.2003.11.018 15199352 | Intervention/exposure; Outcome
352 | Seki, T, Takeuchi, M, Kawakami, K. Eating and drinking habits and its association with obesity in Japanese healthy adults: retrospective longitudinal big data analysis using a health check-up database. Br J Nutr. 2021. 126:1585–1591. doi:10.1017/s0007114521000179.33461638 | Int/Exp: Not relevant
353 | Selmin, Kose, Yildirim, Gulay. The Effect of a Nutrition Education Program on Nutrition Behavior and Body Mass Index of Secondaruy School Students. International Journal of Caring Sciences. 2020. 13:573–582. | Int/Exp: Not relevant
354 | Sen, A, Papadimitriou, N, Lagiou, P, Perez-Cornago, A, Travis, RC, Key, TJ, Murphy, N, Gunter, M, Freisling, H, Tzoulaki, I, Muller, DC, Cross, AJ, Lopez, DS, Bergmann, M, Boeing, H, Bamia, C, Kotanidou, A, Karakatsani, A, Tjønneland, A, Kyrø, C, Outzen, M, Redondo, ML, Cayssials, V, Chirlaque, MD, Barricarte, A, Sánchez, MJ, Larrañaga, N, Tumino, R, Grioni, S, Palli, D, Caini, S, Sacerdote, C, Bueno-de-Mesquita, B, Kühn, T, Kaaks, R, Nilsson, LM, Landberg, R, Wallström, P, Drake, I, Bech, BH, Overvad, K, Aune, D, Khaw, KT, Riboli, E, Trichopoulos, D, Trichopoulou, A, Tsilidis, KK. Coffee and tea consumption and risk of prostate cancer in the European Prospective Investigation into Cancer and Nutrition. Int J Cancer. 2019. 144:240–250. doi:10.1002/ijc.31634 29943826 | Outcome
355 | Sengpiel, V, Elind, E, Bacelis, J, Nilsson, S, Grove, J, Myhre, R, Haugen, M, Meltzer, HM, Alexander, J, Jacobsson, B, Brantsaeter, AL. Maternal caffeine intake during pregnancy is associated with birth weight but not with gestational length: results from a large prospective observational cohort study. BMC Med. 2013. 11:42. doi:10.1186/1741-7015-11-42 23421532 | Population
356 | Sengpiel, V, Elind, E, Bacelis, J, Nilsson, S, Grove, J, Myhre, R, Haugen, M, Meltzer, HM, Alexander, J, Jacobsson, B, Brantsaeter, AL. Maternal caffeine intake during pregnancy is associated with birth weight but not with gestational length: results from a large prospective observational cohort study. BMC Med. 2013. 11:42. doi:10.1186/1741-7015-11-42 23421532 | Outcome; EXCLUDE
357 | Shang, X, Li, Y, Xu, H, Zhang, Q, Liu, A, Du, S, Guo, H, Ma, G. Leading dietary determinants identified using machine learning techniques and a healthy diet score for changes in cardiometabolic risk factors in children: a longitudinal analysis. Nutr J. 2020. 19:105. doi:10.1186/s12937-020-00611-2.32950062 | Int/Exp: Not relevant; Outcome
358 | Sharifan P, Rashidmayvan M, Khorasanchi Z, Darroudi S, Heidari A, Hoseinpoor F, Vatanparast H, Safarian M, Eslami S, Afshari A, Asadi Z, Ghazizadeh H, Bagherniya M, Khedmatgozar H, Ferns G, Rezaie M, Mobarhan MG. Efficacy of low-fat milk and yogurt fortified with vitamin D(3) on systemic inflammation in adults with abdominal obesity. J Health Popul Nutr. 2022;41(1):8. Published 2022 Mar 2. doi:10.1186/s41043-022-00283-0.35236423 | Comparator; Outcome
359 | Sharifan P, Rashidmayvan M, Khorasanchi Z, Efficacy of low-fat milk and yogurt fortified with vitamin D3 on systemic inflammation in adults with abdominal obesity. J Health Popul Nutr. 2022;41(1):8. Published 2022 Mar 2. doi:10.1186/s41043-022-00283-0 35236423 | Outcome; Other; Duplicate
360 | Sharifan P, Ziaee A, Darroudi S, Effect of low-fat dairy products fortified with 1500IU nano encapsulated vitamin D(3) on cardiometabolic indicators in adults with abdominal obesity: a total blinded randomized controlled trial. Curr Med Res Opin. 2021. 37:579–588. doi:10.1080/03007995.2021.1874324.33434080 | Comparator
361 | Sheng, X, Tong, M, Zhao, D, Leung, TF, Zhang, F, Hays, NP, Ge, J, Ho, WM, Northington, R, Terry, DL, Yao, M. Randomized controlled trial to compare growth parameters and nutrient adequacy in children with picky eating behaviors who received nutritional counseling with or without an oral nutritional supplement. Nutr Metab Insights. 2014. 7:85–94. doi:10.4137/nmi.S15097 25342910 | Intervention/exposure
362 | Shi, L, Shu, XO, Li, H, Cai, H, Liu, Q, Zheng, W, Xiang, YB, Villegas, R. Physical activity, smoking, and alcohol consumption in association with incidence of type 2 diabetes among middle-aged and elderly Chinese men. PLoS One. 2013. 8:e77919. doi:10.1371/journal.pone.0077919 24223743 | Intervention/exposure; Outcome; Country
363 | Shi, Z, Yuan, B, Hu, G, Dai, Y, Zuo, H, Holmboe-Ottesen, G. Dietary pattern and weight change in a 5-year follow-up among Chinese adults: results from the Jiangsu Nutrition Study. Br J Nutr. 2011. 105:1047–54. doi:10.1017/s0007114510004630 21106132 | Intervention/exposure; Country
364 | Shikany, JM, Safford, MM, Newby, PK, Durant, RW, Brown, TM, Judd, SE. Southern Dietary Pattern is Associated With Hazard of Acute Coronary Heart Disease in the Reasons for Geographic and Racial Differences in Stroke (REGARDS) Study. Circulation. 2015. 132:804–14. doi:10.1161/circulationaha.114.014421 26260732 | Intervention/exposure; Outcome
365 | Shin, D, Lee, KW, Song, WO. Dietary Patterns during Pregnancy Are Associated with Risk of Gestational Diabetes Mellitus. Nutrients. 2015. 7:9369–82. doi:10.3390/nu7115472 26569302 | Study design; Outcome
366 | Sichert-Hellert, W, Kersting, M, Manz, F. Fifteen year trends in water intake in German children and adolescents: results of the DONALD Study. Dortmund Nutritional and Anthropometric Longitudinally Designed Study. Acta Paediatr. 2001. 90:732–7.11519974 | Outcome
367 | Sichert-Hellert, W, Kersting, M. Significance of fortified beverages in the long-term diet of German children and adolescents: 15-year results of the DONALD Study. Int J Vitam Nutr Res. 2001. 71:356–63. doi:10.1024/0300-9831.71.6.356 11840840 | Outcome
368 | Simão, TN, Lozovoy, MA, Simão, AN, Oliveira, SR, Venturini, D, Morimoto, HK, Miglioranza, LH, Dichi, I. Reduced-energy cranberry juice increases folic acid and adiponectin and reduces homocysteine and oxidative stress in patients with the metabolic syndrome. Br J Nutr. 2013. 110:1885–94. doi:10.1017/s0007114513001207 23750500 | Duplicate; Other; Included in 2020 DGs
369 | Skeie, G, Sandvær, V, Grimnes, G. Intake of Sugar-Sweetened Beverages in Adolescents from Troms, Norway-The Tromsø Study: Fit Futures. Nutrients. 2019. 11(2):211. doi:10.3390/nu11020211 30678146 | Study design; Outcome
370 | Skreden, M, Bere, E, Sagedal, LR, Vistad, I, Overby, NC. Changes in fruit and vegetable consumption habits from pre-pregnancy to early pregnancy among Norwegian women. BMC Pregnancy Childbirth. 2017. 17:107. doi:10.1186/s12884-017-1291-y 28376732 | Intervention/Exposure; Outcome
371 | Skreden, M, Hillesund, ER, Wills, AK, Brantsaeter, AL, Bere, E, Overby, NC. Adherence to the New Nordic Diet during pregnancy and subsequent maternal weight development: a study conducted in the Norwegian Mother and Child Cohort Study (MoBa). Br J Nutr. 2018. 119:1286–1294. doi:10.1017/s0007114518000776 29770760 | Intervention/Exposure
372 | Slurink IA, Chen L, Magliano DJ, Kupper N, Smeets T, Soedamah-Muthu SS. Dairy product consumption and incident prediabetes in the Australian Diabetes, Obesity and Lifestyle Study with 12 years follow up. J Nutr. 2023;153(6):1742–1752. doi:10.1016/j.tjnut.2023.03.032.37003506 | Outcome
373 | Smith, RB, Edwards, SC, Best, N, Wright, J, Nieuwenhuijsen, MJ, Toledano, MB. Birth Weight, Ethnicity, and Exposure to Trihalomethanes and Haloacetic Acids in Drinking Water during Pregnancy in the Born in Bradford Cohort. Environ Health Perspect. 2016. 124:681–9. doi:10.1289/ehp.1409480 26340797 | Outcome
374 | Soczynska, I, Dai, D, O'Connor, DL, Birken, CS, Maguire, JL. Age of cow milk introduction and growth among 3–5-year-old children. Public Health Nutr. 2021. 24:5436–5442. doi:10.1017/s1368980020001925.32723404 | Int/Exp: Not relevant; Population at Intervention/exposure
375 | Soga, S, Ota, N, Shimotoyodome, A. Reduction in hydroxyhydroquinone from coffee increases postprandial fat utilization in healthy humans: a randomized double-blind, cross-over trial. Biosci Biotechnol Biochem. 2017. 81:1433–1435. doi:10.1080/09168451.2017.1301802 28322128 | Intervention/exposure; EXCLUDE
376 | Spindola Garcez, L, de Sousa Paz Lima, G, de Azevedo Paiva, A, Maria Rebelo Sampaio da Paz, S, Lazaro Gomes, EI, Nunes, VS, Cotta de Faria, E, de Barros-Mazon, S. Serum Retinol Levels in Pregnant Adolescents and Their Relationship with Habitual Food Intake, Infection and Obstetric, Nutritional and Socioeconomic Variables. Nutrients. 2016. 8(11):669. doi:10.3390/nu8110669 27792135 | Intervention/Exposure; Outcome
377 | Stamler, J, Liu, K, Ruth, KJ, Pryer, J, Greenland, P. Eight-year blood pressure change in middle-aged men: relationship to multiple nutrients. Hypertension. 2002. 39:1000–6. doi:10.1161/01.hyp.0000016178.80811.d9 12019283 | Intervention/exposure; Outcome
378 | Stern, D, Mazariegos, M, Ortiz-Panozo, E, Campos, H, Malik, VS, Lajous, M, López-Ridaura, R. Sugar-Sweetened Soda Consumption Increases Diabetes Risk Among Mexican Women. J Nutr. 2019. 149:795–803. doi:10.1093/jn/nxy298 31050751 | Outcome
379 | Storck Lindholm, E, Strandvik, B, Altman, D, Moller, A, Palme Kilander, C. Different fatty acid pattern in breast milk of obese compared to normal-weight mothers. Prostaglandins Leukot Essent Fatty Acids. 2013. 88:211–7. doi:10.1016/j.plefa.2012.11.007 23273824 | Intervention/Exposure; Outcome
380 | Sugita, M, Kapoor, MP, Nishimura, A, Okubo, T. Influence of green tea catechins on oxidative stress metabolites at rest and during exercise in healthy humans. Nutrition. 2016. 32:321–31. doi:10.1016/j.nut.2015.09.005 26695876 | Intervention/exposure; EXCLUDE
381 | Suliga, E, Adamczyk-Gruszka, OK. Health behaviours of pregnant women and gestational weight gains -A pilot study. Medical Studies/Studia Medyczne. 2015. 31:161–167. doi:10.5114/ms.2015.54753 | Study design
382 | Sylvetsky, AC, Figueroa, J, Rother, KI, Goran, MI, Welsh, JA. Trends in Low-Calorie Sweetener Consumption Among Pregnant Women in the United States. Curr Dev Nutr. 2019. 3:nzz004. doi:10.1093/cdn/nzz004 30931427 | Outcome
383 | Szypowska A, Regulska-Ilow B, Zatońska K, Szuba A. Comparison of Intake of Food Groups Based on Dietary Inflammatory Index (DII) and Cardiovascular Risk Factors in the Middle-Age Population of Lower Silesia: Results of the PURE Poland Study. Antioxidants (Basel). 2023;12(2):285. doi:10.3390/antiox12020285.36829844 | Study design; Int/Exp: Not relevant
384 | Takagi, T, Hayashi, R, Nakai, Y, Okada, S, Miyashita, R, Yamada, M, Mihara, Y, Mizushima, K, Morita, M, Uchiyama, K, Naito, Y, Itoh, Y. Dietary Intake of Carotenoid-Rich Vegetables Reduces Visceral Adiposity in Obese Japanese men-A Randomized, Double-Blind Trial. Nutrients. 2020. 12(8):2342. doi:10.3390/nu12082342.32764462 | Int/Exp: Not relevant
385 | Tatullo M, Marrelli B, Benincasa C, Aiello E, Amantea M, Gentile S, Leonardi N, Balestrieri ML, Campanile G. Potential impact of functional biomolecules-enriched foods on human health: A randomized controlled clinical trial. Int J Med Sci. 2022;19(3):563–571. Published 2022 Mar 6. doi:10.7150/ijms.70435.35370460 | Int/Exp: Not relevant
386 | Tebbani, F, Oulamara, H, Agli, A. Food diversity and nutrient intake during pregnancy in relation to maternal weight gain. Nutrition Clinique et Metabolisme. 2021. 35:93–99. doi:10.1016/j.nupar.2020.09.001. | Int/Exp: Not relevant
387 | Tee, LP, Brandreth, RA, Sauven, N, Clarke, L, Frampton, I. Successful outcomes in childrens specialist weight management: Impact assessment of a novel early years weight management programme. J Hum Nutr Diet. 2021. 34:819–826. doi:10.1111/jhn.12872.33894093 | Int/Exp: Not relevant; Comparator
388 | Teixeira, JA, Castro, TG, Grant, CC, Wall, CR, Castro, Alds, Francisco, RPV, Vieira, SE, Saldiva, Srdm, Marchioni, DM. Dietary patterns are influenced by socio-demographic conditions of women in childbearing age: a cohort study of pregnant women. BMC Public Health. 2018. 18:301. doi:10.1186/s12889-018-5184-4 29490638 | Outcome
389 | Ten Haaf DSM, Eijsvogels TMH, Bongers CCWG, Protein supplementation improves lean body mass in physically active older adults: a randomized placebo-controlled trial. J Cachexia Sarcopenia Muscle. 2019;10(2):298–310. doi:10.1002/jcsm.12394 30848096 | Int/Exp: Not relevant
390 | Teo, CH, Chin, YS, Lim, PY, Masrom, SAH, Shariff, ZM. Impacts of a School-Based Intervention That Incorporates Nutrition Education and a Supportive Healthy School Canteen Environment among Primary School Children in Malaysia. Nutrients. 2021. 13:(5):1712. doi:10.3390/nu13051712.34070053 | Int/Exp: Not relevant
391 | Theriault, S, Giguere, Y, Masse, J, Girouard, J, Forest, JC. Early prediction of gestational diabetes: a practical model combining clinical and biochemical markers. Clin Chem Lab Med. 2016. 54:509–18. doi:10.1515/cclm-2015-0537 26351946 | Outcome
392 | Tholstrup, T, Høy, CE, Andersen, LN, Christensen, RD, Sandström, B. Does fat in milk, butter and cheese affect blood lipids and cholesterol differently?. J Am Coll Nutr. 2004. 23:169–76. doi:10.1080/07315724.2004.10719358 15047684 | EXCLUDE
393 | Tollånes, MC, Strandberg-Larsen, K, Eichelberger, KY, Moster, D, Lie, RT, Brantsæter, AL, Meltzer, HM, Stoltenberg, C, Wilcox, AJ. Intake of Caffeinated Soft Drinks before and during Pregnancy, but Not Total Caffeine Intake, Is Associated with Increased Cerebral Palsy Risk in the Norwegian Mother and Child Cohort Study. J Nutr. 2016. 146:1701–6. doi:10.3945/jn.116.232272 27489007 | Outcome
394 | Tonstad, S, Smerud, K, Høie, L. A comparison of the effects of 2 doses of soy protein or casein on serum lipids, serum lipoproteins, and plasma total homocysteine in hypercholesterolemic subjects. Am J Clin Nutr. 2002. 76:78–84. doi:10.1093/ajcn/76.1.78 12081819 | Intervention/exposure
395 | Torjusen, H, Brantsaeter, AL, Haugen, M, Alexander, J, Bakketeig, LS, Lieblein, G, Stigum, H, Naes, T, Swartz, J, Holmboe-Ottesen, G, Roos, G, Meltzer, HM. Reduced risk of preeclampsia with organic vegetable consumption: results from the prospective Norwegian Mother and Child Cohort Study. BMJ Open. 2014. 4:e006143. doi:10.1136/bmjopen-2014-006143 | Intervention/Exposure; Outcome
396 | Torjusen, H, Brantsæter, AL, Haugen, M, Alexander, J, Bakketeig, LS, Lieblein, G, Stigum, H, Næs, T, Swartz, J, Holmboe-Ottesen, G, Roos, G, Meltzer, HM. Reduced risk of preeclampsia with organic vegetable consumption: results from the prospective Norwegian Mother and Child Cohort Study. BMJ Open. 2014. 4:e006143. doi:10.1136/bmjopen-2014-006143 | Intervention/exposure; Outcome
397 | Torres-Collado, L, Garcia-de-la-Hera, M, Navarrete-Muñoz, EM, Notario-Barandiaran, L, Gonzalez-Palacios, S, Zurriaga, O, Melchor, I, Vioque, J. Coffee consumption and mortality from all causes of death, cardiovascular disease and cancer in an elderly Spanish population. Eur J Nutr. 2019. 58:2439–2448. doi:10.1007/s00394-018-1796-9 30066178 | Outcome
398 | Tovar, A, Guthrie, LB, Platek, D, Stuebe, A, Herring, SJ, Oken, E. Modifiable predictors associated with having a gestational weight gain goal. Matern Child Health J. 2011. 15:1119–26. doi:10.1007/s10995-010-0659-7 20711804 | Study design; Outcome
399 | Toxqui, L, Pérez-Granados, AM, Blanco-Rojo, R, Wright, I, de la Piedra, C, Vaquero, MP. Low iron status as a factor of increased bone resorption and effects of an iron and vitamin D-fortified skimmed milk on bone remodelling in young Spanish women. Eur J Nutr. 2014. 53:441–8. doi:10.1007/s00394-013-0544-4 23771807 | Intervention/exposure; Outcome
400 | Toxqui, L, Vaquero, MP. An Intervention with Mineral Water Decreases Cardiometabolic Risk Biomarkers. A Crossover, Randomised, Controlled Trial with Two Mineral Waters in Moderately Hypercholesterolaemic Adults. Nutrients. 2016. 8(7):400. doi:10.3390/nu8070400 27367723 | Intervention/exposure; Outcome
401 | Tryggvadottir, EA, Medek, H, Birgisdottir, BE, Geirsson, RT, Gunnarsdottir, I. Association between healthy maternal dietary pattern and risk for gestational diabetes mellitus. Eur J Clin Nutr. 2016. 70:237–42. doi:10.1038/ejcn.2015.145 26350393 | Outcome
402 | Tugault-Lafleur CN, De-Jongh González O, Macdonald J, Bradbury J, Warshawski T, Ball GDC, Morrison K, Ho J, Hamilton J, Buchholz A, Mâsse L. Efficacy of the Aim2Be Intervention in Changing Lifestyle Behaviors Among Adolescents With Overweight and Obesity: Randomized Controlled Trial. J Med Internet Res. 2023;25:e38545. doi:10.2196/38545.37097726 | Int/Exp: Not relevant
403 | Twisk, JW, Kemper, HC, Van Mechelen, W, Post, GB. Clustering of risk factors for coronary heart disease. the longitudinal relationship with lifestyle. Ann Epidemiol. 2001. 11:157–65. doi:10.1016/s1047-2797(00)00202-7 11248580 | Intervention/exposure
404 | Uerlich, MF, Baker, SR, Day, PF, Brown, L, Vettore, MV. Common Determinants of Dental Caries and Obesity in Children: A Multi-Ethnic Nested Birth Cohort Study in the United Kingdom. Int J Environ Res Public Health. 2021. 18(23):12561. doi:10.3390/ijerph182312561.34886288 | Study design
405 | Van Der Hoeven, T, Browne, JL, Uiterwaal, CSPM, Van Der Ent, CK, Grobbee, DE, Dalmeijer, GW. Antenatal coffee and tea consumption and the effect on birth outcome and hypertensive pregnancy disorders. PLoS ONE. 2017. 12(5):e0177619. doi:10.1371/journal.pone.0177619 28520809 | Outcome
406 | Van Hulst, A, Ybarra, M, Mathieu, ME, Benedetti, A, Paradis, G, Henderson, M. Determinants of new onset cardiometabolic risk among normal weight children. Int J Obes (Lond). 2020. 44:781–789. doi:10.1038/s41366-019-0483-0.31767973 | Outcome
407 | Vandyousefi, S, Whaley, S, Asigbee, F, Landry, M, Ghaddar, R, Davis, J. Association of Breastfeeding and Sugar-Sweetened Beverage Consumption with Obesity Prevalence in Offspring Born to Mothers with and Without Gestational Diabetes Mellitus (P11–098-19). Curr Dev Nutr. 2019. 3:1070. doi:10.1093/cdn/nzz048.P11-098-19 | Pub status
408 | Viana Dias JP, Pimenta AM, de Souza Costa Sobrinho P, Miranda Hermsdorff HH, Bressan J, Nobre LN. Consumption of sweetened beverages is associated with the incidence of type 2 diabetes in Brazilian adults (CUME project). Nutr Metab Cardiovasc Dis. 2023;33(4):789–796. doi:10.1016/j.numecd.2023.01.022 36849319 | Outcome
409 | Vilela, AA, Pinto Tde, J, Rebelo, F, Benaim, C, Lepsch, J, Dias-Silva, CH, Castro, MB, Kac, G. Association of Prepregnancy Dietary Patterns and Anxiety Symptoms from Midpregnancy to Early Postpartum in a Prospective Cohort of Brazilian Women. J Acad Nutr Diet. 2015. 115:1626–35. doi:10.1016/j.jand.2015.01.007 25769749 | Intervention/Exposure; Outcome
410 | Villegas, R, Gao, YT, Dai, Q, Yang, G, Cai, H, Li, H, Zheng, W, Shu, XO. Dietary calcium and magnesium intakes and the risk of type 2 diabetes: the Shanghai Women's Health Study. Am J Clin Nutr. 2009. 89:1059–67. doi:10.3945/ajcn.2008.27182 19225116 | Outcome; Country
411 | Villegas, R, Gao, YT, Yang, G, Li, HL, Elasy, TA, Zheng, W, Shu, XO. Legume and soy food intake and the incidence of type 2 diabetes in the Shanghai Women's Health Study. Am J Clin Nutr. 2008. 87:162–7. doi:10.1093/ajcn/87.1.162 18175751 | Outcome; Country
412 | Vitti, FP, Grandi, C, Cavalli, RC, Simoes, VMF, Batista, RFL, Cardoso, VC. Association between Caffeine Consumption in Pregnancy and Low Birth Weight and Preterm Birth in the birth Cohort of Ribeirao Preto. Rev Bras Ginecol Obstet. 2018. 40:749–756. doi:10.1055/s-00381675806 30536269 | Intervention/Exposure; Outcome
413 | Vitti, FP, Grandi, C, Cavalli, RC, Simões, VMF, Batista, RFL, Cardoso, VC. Association between Caffeine Consumption in Pregnancy and Low Birth Weight and Preterm Birth in the birth Cohort of Ribeirão Preto. Rev Bras Ginecol Obstet. 2018. 40:749–756. doi:10.1055/s-00381675806 30536269 | Study design; Outcome
414 | Voerman, E, Jaddoe, VW, Gishti, O, Hofman, A, Franco, OH, Gaillard, R. Maternal caffeine intake during pregnancy, early growth, and body fat distribution at school age. Obesity (Silver Spring). 2016. 24:1170–7. doi:10.1002/oby.21466 27015969 | Outcome; Population
415 | Voidazan, S, Tarcea, M, Abram, Z, Georgescu, M, Marginean, C, Grama, O, Buicu, F, Ruţa, F. Associations between lifestyle factors and smoking status during pregnancy in a group of Romanian women. Birth Defects Research. 2018. 110:519–526. doi:10.1002/bdr2.1190 29318743 | Outcome
416 | Wall, CR, Hill, RJ, Lovell, AL, Matsuyama, M, Milne, T, Grant, CC, Jiang, Y, Chen, RX, Wouldes, TA, Davies, PSW. A multicenter, double-blind, randomized, placebo-controlled trial to evaluate the effect of consuming Growing Up Milk "lite" on body composition in children aged 12–23 mo. American Journal of Clinical Nutrition. 2019. 109:526–534. doi:10.1093/ajcn/nqy302.30698631 | Population at Intervention/exposure
417 | Wang C, Sun J, Hui Z, Consumption frequencies of beverages and the hypertension risk in adults: a cohort study in China. BMJ Open. 2023;13(4):e072474. doi:10.1136/bmjopen-2023-072474 | Outcome
418 | Wang, ML, Otis, M, Rosal, MC, Griecci, CF, Lemon, SC. Reducing sugary drink intake through youth empowerment: results from a pilot-site randomized study. Int J Behav Nutr Phys Act. 2019. 16:58. doi:10.1186/s12966-019-0819-0.31362753 | Int/Exp: Not relevant; Outcome; EXCLUDE
419 | Wang, XY, Liu, FC, Yang, XL, Li, JX, Cao, J, Lu, XF, Huang, JF, Li, Y, Chen, JC, Zhao, LC, Shen, C, Hu, DS, Zhao, YX, Yu, L, Liu, XQ, Wu, XP, Gu, DF. Association of cardiovascular diseases with milk intake among general Chinese adults. Chin Med J (Engl). 2020. 133:1144–1154. doi:10.1097/cm9.0000000000000786.32433046 | Outcome
420 | Watanabe, T, Kobayashi, S, Yamaguchi, T, Hibi, M, Fukuhara, I, Osaki, N. Coffee Abundant in Chlorogenic Acids Reduces Abdominal Fat in Overweight Adults: A Randomized, Double-Blind, Controlled Trial. Nutrients. 2019. 11(7):1617. doi:10.3390/nu11071617.31315279 | Int/Exp: Not relevant
421 | Watson, PE, McDonald, BW. Water and nutrient intake in pregnant New Zealand women: association with wheeze in their infants at 18 months. Asia Pac J Clin Nutr. 2014. 23:660–70. doi:10.6133/apjcn.2014.23.4.13 25516325 | Outcome; Population
422 | Watson, PE, McDonald, BW. Water and nutrient intake in pregnant New Zealand women: association with wheeze in their infants at 18 months. Asia Pac J Clin Nutr. 2014. 23:660–70. doi:10.6133/apjcn.2014.23.4.13 25516325 | Outcome
423 | Wei, X, He, JR, Lin, Y, Lu, M, Zhou, Q, Li, S, Lu, J, Yuan, M, Chen, N, Zhang, L, Qiu, L, Mai, W, Pan, Y, Yin, C, Hu, C, Xia, H, Qiu, X. The influence of maternal dietary patterns on gestational weight gain: A large prospective cohort study in China. Nutrition. 2019. 59:90–95. doi:10.1016/j.nut.2018.07.113 30471529 | Intervention/Exposure; Comparator
424 | Wen, LM, Flood, VM, Simpson, JM, Rissel, C, Baur, LA. Dietary behaviours during pregnancy: findings from first-time mothers in southwest Sydney, Australia. International Journal of Behavioral Nutrition & Physical Activity. 2010. 7:7p–7p. doi:10.1186/1479-5868-7-13 20181017 | Study design; Outcome
425 | Wen, LM, Simpson, JM, Rissel, C, Baur, LA. Maternal "junk food" diet during pregnancy as a predictor of high birthweight: findings from the healthy beginnings trial. Birth. 2013. 40:46–51. doi:10.1111/birt.12028 24635424 | Outcome; Population
426 | Wheaton N, Millar L, Allender S, Nichols M. The stability of weight status through the early to middle childhood years in Australia: a longitudinal study. BMJ Open. 2015;5(4):e006963. Published 2015 Apr 28. doi:10.1136/bmjopen-2014-006963 | Duplicate
427 | Whitaker, KM, Marino, RC, Haapala, JL, Foster, L, Smith, KD, Teague, AM, Jacobs, DR, Fontaine, PL, McGovern, PM, Schoenfuss, TC, Harnack, L, Fields, DA, Demerath, EW. Associations of Maternal Weight Status Before, During, and After Pregnancy with Inflammatory Markers in Breast Milk. Obesity (Silver Spring). 2018. 26:1659–1660. doi:10.1002/oby.22278 30277026 | Intervention/Exposure; Outcome
428 | Wierzejska, R, Jarosz, M, Wojda, B. Caffeine Intake During Pregnancy and Neonatal Anthropometric Parameters. Nutrients. 2019. 11(4):806. doi:10.3390/nu11040806 30970673 | Outcome
429 | Wild, CEK, Wynter, LE, Triggs, CM, Derraik, JGB, Hofman, PL, Anderson, YC. Five-year follow-up of a family-based multidisciplinary program for children with obesity. Obesity (Silver Spring). 2021. 29:1458–1468. doi:10.1002/oby.23225.34370401 | Int/Exp: Not relevant
430 | Wilunda, C, Sawada, N, Goto, A, Yamaji, T, Takachi, R, Ishihara, J, Mori, N, Kotemori, A, Iwasaki, M, Tsugane, S. Associations between changes in fruit and vegetable consumption and weight change in Japanese adults. European Journal of Nutrition. 2021. 60:217–227. doi:10.1007/s00394-020-02236-x.32253544 | Int/Exp: Not relevant
431 | Wojcicki, JM, Lustig, RH, Jacobs, LM, Mason, AE, Hartman, A, Leung, C, Stanhope, K, Lin, J, Schmidt, LA, Epel, ES. Longer Leukocyte Telomere Length Predicts Stronger Response to a Workplace Sugar-Sweetened Beverage Sales Ban: An Exploratory Study. Curr Dev Nutr. 2021. 5:nzab084. doi:10.1093/cdn/nzab084.34235373 | Int/Exp: Not relevant; Outcome
432 | Wojcicki, JM, Tsuchiya, KJ, Murakami, K, Ishikuro, M, Obara, T, Morisaki, N. Limited consumption of 100% fruit juices and sugar sweetened beverages in Japanese toddler and preschool children. Prev Med Rep. 2021. 23:101409. doi:10.1016/j.pmedr.2021.101409.34189018 | Outcome
433 | Wong, EY, James, AP, Lee, AH, Jancey, J. Effectiveness of a Singaporean Community-Based Physical Activity and Nutrition Intervention: A Cluster Randomized Controlled Trial. Asia Pac J Public Health. 2021. 33:196–204. doi:10.1177/1010539520977311.33287553 | Int/Exp: Not relevant
434 | Wong, VCH, Maguire, JL, Omand, JA, Dai, DWH, Lebovic, G, Parkin, PC, O'Connor, DL, Birken, CS. A Positive Association Between Dietary Intake of Higher Cow's Milk-Fat Percentage and Non-High-Density Lipoprotein Cholesterol in Young Children. J Pediatr. 2019. 211:105–111.e2. doi:10.1016/j.jpeds.2019.03.047.31104850 | Outcome
435 | Wright, JM, Hoffman, CS, Savitz, DA. The relationship between water intake and foetal growth and preterm delivery in a prospective cohort study. BMC Pregnancy Childbirth. 2010. 10:48. doi:10.1186/1471-2393-10-48 20735835 | Outcome; Population
436 | Wright, LS, Rifas-Shiman, SL, Oken, E, Litonjua, AA, Gold, DR. Prenatal and Early Life Fructose, Fructose-Containing Beverages, and Midchildhood Asthma. Ann Am Thorac Soc. 2018. 15:217–224. doi:10.1513/AnnalsATS.201707-530OC 29219619 | Outcome
437 | Wrottesley, SV, Stacey, N, Mukoma, G, Hofman, KJ, Norris, SA. Assessing sugar-sweetened beverage intakes, added sugar intakes and BMI before and after the implementation of a sugar-sweetened beverage tax in South Africa. Public Health Nutr. 2021. 24:2900–2910. doi:10.1017/s1368980020005078.33315006 | Country
438 | Wu, AJ, Aris, IM, Rifas-Shiman, SL, Oken, E, Taveras, EM, Hivert, MF. Longitudinal associations of fruit juice intake in infancy with DXA-measured abdominal adiposity in mid-childhood and early adolescence. Am J Clin Nutr. 2021. 114:117–123. doi:10.1093/ajcn/nqab043.33829237 | Population at Intervention/exposure
439 | Wuni R, Lakshmipriya N, Abirami K, Higher Intake of Dairy Is Associated with Lower Cardiometabolic Risks and Metabolic Syndrome in Asian Indians. Nutrients. 2022;14(18):3699. Published 2022 Sep 7. doi:10.3390/nu14183699 36145074 | Int/Exp: Not relevant; Country
440 | Xie, Y, Madkour, AS, Harville, EW. Preconception Nutrition, Physical Activity, and Birth Outcomes in Adolescent Girls. J Pediatr Adolesc Gynecol. 2015. 28:471–6. doi:10.1016/j.jpag.2015.01.004 26233291 | Outcome; Population
441 | Yamakawa, M, Wada, K, Koda, S, Mizuta, F, Uji, T, Oba, S, Nagata, C. High Intake of Free Sugars, Fructose, and Sucrose Is Associated with Weight Gain in Japanese Men. J Nutr. 2020. 150:322–330. doi:10.1093/jn/nxz227.31532489 | Int/Exp: Not relevant
442 | Yan T, Shi L, Xu K, Bai J, Wen R, Liao X, Dai X, Wu Q, Zeng L, Peng W, Wang Y, Yan H, Dang S, Liu X. Habitual intakes of sugar-sweetened beverages associated with gut microbiota-related metabolites and metabolic health outcomes in young Chinese adults. Nutr Metab Cardiovasc Dis. 2023;33(2):359–368. doi:10.1016/j.numecd.2022.10.016.36577637 | Study design
443 | Yang Y, Na X, Xi Y, Xi M, Yang H, Li Z, Zhao A. Association between dairy consumption and the risk of diabetes: A prospective cohort study from the China Health and Nutrition Survey. Front Nutr. 2022;9:997636. doi:10.3389/fnut.2022.997636.36225884 | Int/Exp: Not relevant; Outcome
444 | Yapici H, Gülü M, Yagin FH, Ugurlu D, Comertpay E, Eroglu O, Kocoğlu M, Aldhahi MI, Karayigit R, Badri Al-Mhanna S. The effect of 8-weeks of combined resistance training and chocolate milk consumption on maximal strength, muscle thickness, peak power and lean mass, untrained, university-aged males. Front Physiol. 2023;14:1148494. doi:10.3389/fphys.2023.1148494.37007992 | EXCLUDE
445 | Yong, HY, Shariff, ZM, Mohd Yusof, BN, Rejali, Z, Bindels, J, Tee, YYS, van der Beek, EM. Associations between the dietary patterns of pregnant Malaysian women and ethnicity, education, and early pregnancy waist circumference: A prospective cohort study. Nutr Res Pract. 2019. 13:230–239. doi:10.4162/nrp.2019.13.3.230 31214291 | Intervention/Exposure; Outcome
446 | Yoon, Lara, Corvalán, Camila, Pereira, Ana, Shepherd, John, Michels, KarinB. Sugarsweetened beverage consumption and breast composition in a longitudinal study of Chilean girls. Breast Cancer Research. 2022. 24:1–11. doi: 10.1186/s13058-021-01495-8.34983617 | Duplicate
447 | Yoon, Lara, Corvalán, Camila, Pereira, Ana, Shepherd, John, Michels, KarinB. Sugarsweetened beverage consumption and breast composition in a longitudinal study of Chilean girls. Breast Cancer Research. 2022. 24:1–11. doi:10.1186/s13058-021-01495-8.34983617 | Other; Duplicate
448 | Yoshitomi, R, Yamamoto, M, Kumazoe, M, Fujimura, Y, Yonekura, M, Shimamoto, Y, Nakasone, A, Kondo, S, Hattori, H, Haseda, A, Nishihira, J, Tachibana, H. The combined effect of green tea and α-glucosyl hesperidin in preventing obesity: a randomized placebocontrolled clinical trial. Sci Rep. 2021. 11:19067. doi:10.1038/s41598-021-98612-6.34561541 | Int/Exp: Not relevant
449 | Younis, NT, Abdulmawjood, SA. The Effectiveness of Soft Drinks on Some Biochemical Variables in Human Body. Biochemical and Cellular Archives. 2021.21:1069–1073. | Study design; Country
450 | Yu, D, Shu, XO, Li, H, Xiang, YB, Yang, G, Gao, YT, Zheng, W, Zhang, X. Dietary carbohydrates, refined grains, glycemic load, and risk of coronary heart disease in Chinese adults. Am J Epidemiol. 2013. 178:1542–9. doi: 10.1093/aje/kwt178 24008907 | Intervention/exposure; Country
451 | Yuan S, Sun J, Lu Y, Xu F, Li D, Jiang F, Wan Z, Li X, Qin LQ, Larsson SC. Health effects of milk consumption: phenome-wide Mendelian randomization study. BMC Med. 2022;20(1):455. doi:10.1186/s12916-022-02658-w.36424608 | Study design; Outcome
452 | Yuan, S, Carter, P, Mason, AM, Burgess, S, Larsson, SC. Coffee Consumption and Cardiovascular Diseases: A Mendelian Randomization Study. Nutrients. 2021. 13(7):2218. doi:10.3390/nu13072218.34203356 | Outcome
453 | Zapata-Londoño, MB, Ramos Polo, A, Alzate-Arbelaez, AF, Restrepo-Betancur, LF, Rojano, BA, Maldonado-Celis, ME. Effect of mango (Mangifera indica) cv. azÚcar juice consumption on plasma antioxidant capacity and oxidative stress biomarkers. Vitae. 2020. 27:1–10. doi:10.17533/udea.vitae.v27n1a03. | Outcome
454 | Zefreei, AA, Taghian, F, Dehkordi, KJ. Effect of 8 weeks aerobic exercises and green coffee supplement on serum myonectin, meteorin-like, and insulin resistance in obese women. Journal of mazandaran university of medical sciences. 2020. 30:58–67. | Language
455 | Zhang Y, Liu C, Xu Y, Wang Y, Zhang Y, Jiang T, Zhang Q. The relationship between sugar-sweetened beverages, sleep disorders, and diabesity. Front Endocrinol (Lausanne). 2023;13:1041977. Published 2023 Jan 9. doi:10.3389/fendo.2022.1041977.36699031 | Study design
456 | Zhang, J, Oxinos, G, Maher, JH. The effect of fruit and vegetable powder mix on hypertensive subjects: a pilot study. J Chiropr Med. 2009. 8:101–6. doi: 10.1016/j.jcm.2008.09.004 19703665 | Intervention/exposure; Outcome
457 | Zhang, X, Li, L, Xu, J, Xu, P, Yang, T, Gan, Q, Pan, H, Hu, X, Cao, W, Zhang, Q. Association between milk consumption and the nutritional status of poor rural Chinese students in 2016. Asia Pac J Clin Nutr. 2020. 29:813–820. doi:10.6133/apjcn.202012_29(4).0017.33377376 | Study design; Int/Exp: Not relevant
458 | Zheng M, Rangan A, Allman-Farinelli M, Rohde JF, Olsen NJ, Heitmann BL. Replacing sugary drinks with milk is inversely associated with weight gain among young obesity-predisposed children. Br J Nutr. 2015;114(9): 1448–1455. doi: 10.1017/S0007114515002974 26328600 | Duplicate
459 | Zhou, B, Ichikawa, R, Parnell, LD, Noel, SE, Zhang, X, Bhupathiraju, SN, Smith, CE, Tucker, KL, Ordovas, JM, Lai, CQ. Metabolomic Links between Sugar-Sweetened Beverage Intake and Obesity. J Obes. 2020. 2020:7154738. doi:10.1155/2020/7154738.32399287 | Study design
460 | Zhu, K, Greenfield, H, Du, X, Zhang, Q, Ma, G, Hu, X, Cowell, CT, Fraser, DR. Effects of two years' milk supplementation on size-corrected bone mineral density of Chinese girls. Asia Pac J Clin Nutr. 2008. 17 Suppl 1:147–50.18296324 | Outcome; Country
461 | Zhu, K, Greenfield, H, Zhang, Q, Du, X, Ma, G, Foo, LH, Cowell, CT, Fraser, DR. Growth and bone mineral accretion during puberty in Chinese girls: a five-year longitudinal study. J Bone Miner Res. 2008. 23:167–72. doi:10.1359/jbmr.071006 17907923 | Intervention/exposure; Country
462 | Zhu, Y, Olsen, SF, Mendola, P, Halldorsson, TI, Rawal, S, Hinkle, SN, Yeung, EH, Chavarro, JE, Grunnet, LG, Granstrom, C, Bjerregaard, AA, Hu, FB, Zhang, C. Maternal consumption of artificially sweetened beverages during pregnancy, and offspring growth through 7 years of age: a prospective cohort study. Int J Epidemiol. 2017. 46:1499–1508. doi:10.1093/ije/dyx095 28586472 | Outcome; Population
463 | Zulfiqar, T, Strazdins, L, Dinh, H, Banwell, C, D'Este, C. Drivers of Overweight/Obesity in 4–11 Year Old Children of Australians and Immigrants; Evidence from Growing Up in Australia. J Immigr Minor Health. 2019. 21:737–750. doi:10.1007/s10903-018-0841-3.30484000 | Duplicate