# Appendix 2 Conclusion statements from the existing systematic review

Table A 2 Conclusion statements from the existing systematic review for the research question: What is the relationship between low- and no-calorie sweetened beverage consumption and growth, body composition, and risk of obesity?

Citation | Conclusion statements and grades
Mayer-Davis E, Leidy H, Mattes R, Naimi T, Novotny R, Schneeman B, Kingshipp BJ, Spill M, Cole NC, Bahnfleth CL, Butera G, Terry N, Obbagy J. Beverage Consumption and Growth, Size, Body Composition, and Risk of Overweight and Obesity: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0401 | Limited evidence suggests no association between low- and no-calorie sweetened beverage consumption and adiposity in children. (Grade: Limited); Limited evidence suggests that low- and no-calorie sweetened beverage consumption is associated with reduced adiposity in adults. (Grade: Limited)