# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
BMIZ: BMI z-score
FNS: Food and Nutrition Service
HDI: Human development index
HHS: United States Department of Health and Human Services
LNCSB: Low- and no-calorie sweetened beverage
NESR: Nutrition Evidence Systematic Review
NGAD: Nutrition Guidance and Analysis Division
PCS: Prospective cohort study
RCT: Randomized controlled trial
SEP: Socioeconomic position
SSB: Sugar sweetened beverages
TEI: Total energy intake
USDA: United States Department of Agriculture