# References of the articles included in the systematic review

1 Arnberg K, Molgaard C, Michaelsen KF, Jensen SM, Trolle E, Larnkjaer A. Skim milk, whey, and casein increase body weight and whey and casein increase the plasma C-peptide concentration in overweight adolescents. J Nutr. Dec 2012;142(12):2083–90. doi:10.3945/jn.112.161208 23077192
2 Lambourne K, Washburn RA, Lee J, A 6-month trial of resistance training with milk supplementation in adolescents: effects on body composition. Int J Sport Nutr Exerc Metab. Aug 2013;23(4):344–56. doi:10.1123/ijsnem.23.4.344 23239680
3 Larnkjaer A, Arnberg K, Michaelsen KF, Jensen SM, Molgaard C. Effect of milk proteins on linear growth and IGF variables in overweight adolescents. Growth Horm IGF Res. Apr-Jun 2014;24(2–3):54–9. doi:10.1016/j.ghir.2013.12.004 24461794
4 Larnkjaer A, Arnberg K, Michaelsen KF, Jensen SM, Molgaard C. Effect of increased intake of skimmed milk, casein, whey or water on body composition and leptin in overweight adolescents: a randomized trial. Pediatr Obes. Dec 2015;10(6):461–7. doi:10.1111/ijpo.12007 25612082
5 Rahmani K, Djazayery A, Habibi MI, Effects of daily milk supplementation on improving the physical and mental function as well as school performance among children: results from a school feeding program. J Res Med Sci. Apr 2011;16(4):469–76.22091261
6 Gomez AL, Kraemer WJ, Maresh CM, Resistance Training and Milk-Substitution Enhance Body Composition and Bone Health in Adolescent Girls. J Am Coll Nutr. Mar-Apr 2021;40(3):193–210. doi:10.1080/07315724.2020.1770636 32521207
7 Berkey CS, Colditz GA, Rockett HR, Frazier AL, Willett WC. Dairy consumption and female height growth: prospective cohort study. Cancer Epidemiol Biomarkers Prev. Jun 2009;18(6):1881–7. doi:10.1158/1055-9965.EPI-08-1163 19505921
8 Berkey CS, Rockett HR, Field AE, Gillman MW, Colditz GA. Sugar-added beverages and adolescent weight change. Obes Res. May 2004;12(5):778–88. doi:10.1038/oby.2004.94 15166298
9 Berkey CS, Rockett HR, Willett WC, Colditz GA. Milk, dairy fat, dietary calcium, and weight gain: a longitudinal study of adolescents. Arch Pediatr Adolesc Med. Jun 2005;159(6):543–50. doi:10.1001/archpedi.159.6.543 15939853
10 Blum JW, Jacobsen DJ, Donnelly JE. Beverage consumption patterns in elementary school aged children across a two-year period. J Am Coll Nutr. Apr 2005;24(2):93–8. doi:10.1080/07315724.2005.10719449 15798075
11 Choi MJ, Kang H, Choi J. Risk Factors for Obesity in Five-Year-Old Children: Based on Korean National Health Insurance Service (NHIS) Data. Children (Basel). Feb 25 2022;9(3)doi:10.3390/children9030314
12 DeBoer MD, Agard HE, Scharf RJ. Milk intake, height and body mass index in preschool children. Arch Dis Child. May 2015;100(5):460–5. doi:10.1136/archdischild-2014-306958 25512962
13 Dubois L, Diasparra M, Bogl LH, Dietary Intake at 9 Years and Subsequent Body Mass Index in Adolescent Boys and Girls: A Study of Monozygotic Twin Pairs. Twin Res Hum Genet. Feb 2016;19(1):47–59. doi:10.1017/thg.2015.97 26810866
14 Faith MS, Dennison BA, Edmunds LS, Stratton HH. Fruit juice intake predicts increased adiposity gain in children from low-income families: weight status-by-environment interaction. Pediatrics. Nov 2006;118(5):2066–75. doi:10.1542/peds.2006-1117 17079580
15 Fiorito LM, Marini M, Francis LA, Smiciklas-Wright H, Birch LL. Beverage intake of girls at age 5 y predicts adiposity and weight status in childhood and adolescence. Am J Clin Nutr. Oct 2009;90(4):935–42. doi:10.3945/ajcn.2009.27623 19692492
16 Haines J, Neumark-Sztainer D, Wall M, Story M. Personal, behavioral, and environmental risk and protective factors for adolescent overweight. Obesity (Silver Spring). Nov 2007;15(11):2748–60. doi:10.1038/oby.2007.327 18070766
17 Hasnain SR, Singer MR, Bradlee ML, Moore LL. Beverage intake in early childhood and change in body fat from preschool to adolescence. Child Obes. Feb 2014;10(1):42–9. doi:10.1089/chi.2013.0004 24450382
18 Huh SY, Rifas-Shiman SL, Rich-Edwards JW, Taveras EM, Gillman MW. Prospective association between milk intake and adiposity in preschool-aged children. J Am Diet Assoc. Apr 2010;110(4):563–70. doi:10.1016/j.jada.2009.12.025 20338282
19 Johnson L, Mander AP, Jones LR, Emmett PM, Jebb SA. Is sugar-sweetened beverage consumption associated with increased fatness in children? Nutrition. Jul-Aug 2007;23(7–8):557–63. doi:10.1016/j.nut.2007.05.005 17616342
20 Kral TV, Stunkard AJ, Berkowitz RI, Stallings VA, Moore RH, Faith MS. Beverage consumption patterns of children born at different risk of obesity. Obesity (Silver Spring). Aug 2008;16(8):1802–8. doi:10.1038/oby.2008.287 18535546
21 Kunaratnam K, Halaki M, Wen LM, Baur LA, Flood VM. Tracking Preschoolers' Lifestyle Behaviors and Testing Maternal Sociodemographics and BMI in Predicting Child Obesity Risk. J Nutr. Dec 10 2020;150(12):3068–3074. doi:10.1093/jn/nxaa292 33096560
22 Laurson K, Eisenmann JC, Moore S. Lack of association between television viewing, soft drinks, physical activity and body mass index in children. Acta Paediatr. Jun 2008;97(6):795–800. doi:10.1111/j.1651-2227.2008.00713.x 18410467
23 Lin SL, Tarrant M, Hui LL, The role of dairy products and milk in adolescent obesity: evidence from Hong Kong's "Children of 1997" birth cohort. PLoS One. 2012;7(12):e52575. doi:10.1371/journal.pone.0052575 23285099
24 Marabujo T, Ramos E, Lopes C. Dairy products and total calcium intake at 13 years of age and its association with obesity at 21 years of age. Eur J Clin Nutr. Apr 2018;72(4):541–547. doi:10.1038/s41430-017-0082-x 29371641
25 Marshall TA, Curtis AM, Cavanaugh JE, Warren JJ, Levy SM. Higher Longitudinal Milk Intakes Are Associated with Increased Height in a Birth Cohort Followed for 17 Years. J Nutr. Jul 1 2018;148(7):1144–1149. doi:10.1093/jn/nxy071 29924327
26 Marshall TA, Curtis AM, Cavanaugh JE, Warren JJ, Levy SM. Child and Adolescent Sugar-Sweetened Beverage Intakes Are Longitudinally Associated with Higher Body Mass Index z Scores in a Birth Cohort Followed 17 Years. J Acad Nutr Diet. Mar 2019;119(3):425–434. doi:10.1016/j.jand.2018.11.003 30638821
27 Newby PK, Peterson KE, Berkey CS, Leppert J, Willett WC, Colditz GA. Beverage consumption is not associated with changes in weight and body mass index among low-income preschool children in North Dakota. J Am Diet Assoc. Jul 2004;104(7):1086–94. doi:10.1016/j.jada.2004.04.020 15215766
28 Noel SE, Ness AR, Northstone K, Emmett P, Newby PK. Milk intakes are not associated with percent body fat in children from ages 10 to 13 years. J Nutr. Nov 2011;141(11):2035–41. doi:10.3945/jn.111.143420 21940511
29 Sakaki JR, Li J, Gao S, Associations between fruit juice and milk consumption and change in BMI in a large prospective cohort of U.S. adolescents and preadolescents. Pediatr Obes. Sep 2021;16(9):e12781. doi:10.1111/ijpo.12781 33648027
30 Striegel-Moore RH, Thompson D, Affenito SG, Correlates of beverage intake in adolescent girls: the National Heart, Lung, and Blood Institute Growth and Health Study. J Pediatr. Feb 2006;148(2):183–7. doi:10.1016/j.jpeds.2005.11.025 16492426
31 Tam CS, Garnett SP, Cowell CT, Campbell K, Cabrera G, Baur LA. Soft drink consumption and excess weight gain in Australian school students: results from the Nepean study. Int J Obes (Lond). Jul 2006;30(7):1091–3. doi:10.1038/sj.ijo.0803328 16801946
32 Zheng M, Allman-Farinelli M, Heitmann BL, Liquid versus solid energy intake in relation to body composition among Australian children. J Hum Nutr Diet. Feb 2015;28 Suppl 2:70–9. doi:10.1111/jhn.12223 24548259
33 Zheng M, Rangan A, Allman-Farinelli M, Rohde JF, Olsen NJ, Heitmann BL. Replacing sugary drinks with milk is inversely associated with weight gain among young obesity-predisposed children. Br J Nutr. Nov 14 2015;114(9):1448–55. doi:10.1017/S0007114515002974 26328600
34 Zheng M, Rangan A, Olsen NJ, Substituting sugar-sweetened beverages with water or milk is inversely associated with body fatness development from childhood to adolescence. Nutrition. Jan 2015;31(1):38–44. doi:10.1016/j.nut.2014.04.017 25441586
35 McGovern C, Rifas-Shiman SL, Switkowski KM, Association of cow's milk intake in early childhood with adiposity and cardiometabolic risk in early adolescence. Am J Clin Nutr. Aug 4 2022;116(2):561–571. doi:10.1093/ajcn/nqac103 35441227
36 Dong D, Bilger M, van Dam RM, Finkelstein EA. Consumption Of Specific Foods And Beverages And Excess Weight Gain Among Children And Adolescents. Health Aff (Millwood). Nov 2015;34(11):1940–8. doi:10.1377/hlthaff.2015.0434 26526253
37 Vanselow MS, Pereira MA, Neumark-Sztainer D, Raatz SK. Adolescent beverage habits and changes in weight over time: findings from Project EAT. Am J Clin Nutr. Dec 2009;90(6):1489–95. doi:10.3945/ajcn.2009.27573 19864412
38 Ho SC, Guldan GS, Woo J, A prospective study of the effects of 1-year calcium-fortified soy milk supplementation on dietary calcium intake and bone health in Chinese adolescent girls aged 14 to 16. Osteoporos Int. Dec 2005;16(12):1907–16. doi:10.1007/s00198-005-1963-8 16133646
39 Scharf RJ, Demmer RT, DeBoer MD. Longitudinal evaluation of milk type consumed and weight status in preschoolers. Arch Dis Child. May 2013;98(5):335–40. doi:10.1136/archdischild-2012-302941 23508869
40 Whetstone LM, Kolasa KM, Collier DN. Participation in community-originated interventions is associated with positive changes in weight status and health behaviors in youth. Am J Health Promot. Sep-Oct 2012;27(1):10–6. doi:10.4278/ajhp.100415-QUAN-117 22950920
41 Vanderhout SM, Keown-Stoneman CDG, Birken CS, O'Connor DL, Thorpe KE, Maguire JL. Cow's milk fat and child adiposity: a prospective cohort study. Int J Obes (Lond). Dec 2021;45(12):2623–2628. doi:10.1038/s41366-021-00948-6 34433906
42 Noel SE, Ness AR, Northstone K, Emmett P, Newby PK. Associations between flavored milk consumption and changes in weight and body composition over time: differences among normal and overweight children. Eur J Clin Nutr. Mar 2013;67(3):295–300. doi:10.1038/ejcn.2012.123 23031848
43 Wrotniak BH, Georger L, Hill DL, Zemel BS, Stettler N. Association of dairy intake with weight change in adolescents undergoing obesity treatment. J Public Health (Oxf). Jun 1 2019;41(2):338–345. doi:10.1093/pubmed/fdy064 29659918
44 Barr SI, McCarron DA, Heaney RP, Effects of increased consumption of fluid milk on energy and nutrient intake, body weight, and cardiovascular risk factors in healthy older adults. J Am Diet Assoc. Jul 2000;100(7):810–7. doi:10.1016/S0002-8223(00)00236-4 10916520
45 Chee WS, Suriah AR, Chan SP, Zaitun Y, Chan YM. The effect of milk supplementation on bone mineral density in postmenopausal Chinese women in Malaysia. Osteoporos Int. Oct 2003;14(10):828–34. doi:10.1007/s00198-003-1448-6 12915959
46 Chiang FY, Chen JR, Lee WJ, Yang SC. Effects of Milk or Soy Milk Combined with Mild Resistance Exercise on the Muscle Mass and Muscle Strength in Very Old Nursing Home Residents with Sarcopenia. Foods. Oct 26 2021;10(11)doi:10.3390/foods10112581
47 Daly RM, Brown M, Bass S, Kukuljan S, Nowson C. Calcium- and vitamin D3-fortified milk reduces bone loss at clinically relevant skeletal sites in older men: a 2-year randomized controlled trial. J Bone Miner Res. Mar 2006;21(3):397–405. doi:10.1359/JBMR.051206 16491287
48 Maersk M, Belza A, Stodkilde-Jorgensen H, Sucrose-sweetened beverages increase fat storage in the liver, muscle, and visceral fat depot: a 6-mo randomized intervention study. Am J Clin Nutr. Feb 2012;95(2):283–9. doi:10.3945/ajcn.111.022533 22205311
49 Rosado JL, Garcia OP, Ronquillo D, Intake of milk with added micronutrients increases the effectiveness of an energy-restricted diet to reduce body weight: a randomized controlled clinical trial in Mexican women. J Am Diet Assoc. Oct 2011;111(10):1507–16. doi:10.1016/j.jada.2011.07.011 21963017
50 Ting GP, Tan SY, Chan SP, A follow-up study on the effects of a milk supplement on bone mineral density of postmenopausal Chinese women in Malaysia. J Nutr Health Aging. Jan-Feb 2007;11(1):69–73.17315084
51 Wagner G, Kindrick S, Hertzler S, DiSilvestro RA. Effects of various forms of calcium on body weight and bone turnover markers in women participating in a weight loss program. J Am Coll Nutr. Oct 2007;26(5):456–61. doi:10.1080/07315724.2007.10719636 17914134
52 Babio N, Becerra-Tomas N, Martinez-Gonzalez MA, Consumption of Yogurt, Low-Fat Milk, and Other Low-Fat Dairy Products Is Associated with Lower Risk of Metabolic Syndrome Incidence in an Elderly Mediterranean Population. J Nutr. Oct 2015;145(10):2308–16. doi:10.3945/jn.115.214593 26290009
53 Bes-Rastrollo M, van Dam RM, Martinez-Gonzalez MA, Li TY, Sampson LL, Hu FB. Prospective study of dietary energy density and weight gain in women. Am J Clin Nutr. Sep 2008;88(3):769–77. doi:10.1093/ajcn/88.3.769 18779295
54 Beydoun MA, Fanelli-Kuczmarski MT, Beydoun HA, Dairy product consumption and its association with metabolic disturbance in a prospective study of urban adults. Br J Nutr. Mar 2018;119(6):706–719. doi:10.1017/S0007114518000028 29553032
55 Chen L, Appel LJ, Loria C, Reduction in consumption of sugar-sweetened beverages is associated with weight loss: the PREMIER trial. Am J Clin Nutr. May 2009;89(5):1299–306. doi:10.3945/ajcn.2008.27240 19339405
56 Drapeau V, Després JP, Bouchard C, Modifications in food-group consumption are related to long-term body-weight changes. Am J Clin Nutr. Jul 2004;80(1):29–37. doi:10.1093/ajcn/80.1.29 15213024
57 Duffey KJ, Gordon-Larsen P, Steffen LM, Jacobs DR, Jr., Popkin BM. Drinking caloric beverages increases the risk of adverse cardiometabolic outcomes in the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. Oct 2010;92(4):954–9. doi:10.3945/ajcn.2010.29478 20702604
58 Funtikova AN, Subirana I, Gomez SF, Soft drink consumption is positively associated with increased waist circumference and 10-year incidence of abdominal obesity in Spanish adults. J Nutr. Feb 2015;145(2):328–34. doi:10.3945/jn.114.205229 25644355
59 Guerendiain M, Villa-Gonzalez E, Barranco-Ruiz Y. Body composition and dairy intake in sedentary employees who participated in a healthy program based on nutrition education and Zumba. Clin Nutr. Oct 2019;38(5):2277–2286. doi:10.1016/j.clnu.2018.09.032 30342932
60 Guo J, Dougkas A, Elwood PC, Givens DI. Dairy Foods and Body Mass Index over 10-Year: Evidence from the Caerphilly Prospective Cohort Study. Nutrients. Oct 16 2018;10(10)doi:10.3390/nu10101515
61 Hasselbalch AL, Heitmann BL, Kyvik KO, Sorensen TI. Associations between dietary intake and body fat independent of genetic and familial environmental background. Int J Obes (Lond). May 2010;34(5):892–8. doi:10.1038/ijo.2010.1 20125102
62 Holmberg S, Thelin A. High dairy fat intake related to less central obesity: a male cohort study with 12 years' follow-up. Scand J Prim Health Care. Jun 2013;31(2):89–94. doi:10.3109/02813432.2012.757070 23320900
63 Johansson I, Nilsson LM, Esberg A, Jansson JH, Winkvist A. Dairy intake revisited - associations between dairy intake and lifestyle related cardio-metabolic risk factors in a high milk consuming population. Nutr J. Nov 22 2018;17(1):110. doi:10.1186/s12937-018-0418-y 30466440
64 Kaikkonen JE, Mikkila V, Juonala M, Factors associated with six-year weight change in young and middle-aged adults in the Young Finns Study. Scand J Clin Lab Invest. Apr 2015;75(2):133–44. doi:10.3109/00365513.2014.992945 25600675
65 Kim D, Kim J. Dairy consumption is associated with a lower incidence of the metabolic syndrome in middle-aged and older Korean adults: the Korean Genome and Epidemiology Study (KoGES). Br J Nutr. Jan 2017;117(1):148–160. doi:10.1017/S000711451600444X 28098053
66 Konieczna J, Romaguera D, Pereira V, Longitudinal association of changes in diet with changes in body weight and waist circumference in subjects at high cardiovascular risk: the PREDIMED trial. Int J Behav Nutr Phys Act. Dec 27 2019;16(1):139. doi:10.1186/s12966-019-0893-3 31882021
67 Lee JH, Lee HS, Kim H, Kwon YJ, Lee JW. Association of milk consumption frequency on muscle mass and strength: an analysis of three representative Korean population studies. Eur J Nutr. Oct 2020;59(7):3257–3267. doi:10.1007/s00394-019-02164-5 31858213
68 Mozaffarian D, Hao T, Rimm EB, Willett WC, Hu FB. Changes in diet and lifestyle and long-term weight gain in women and men. N Engl J Med. Jun 23 2011;364(25):2392–404. doi:10.1056/NEJMoa1014296 21696306
69 Pan A, Malik VS, Hao T, Willett WC, Mozaffarian D, Hu FB. Changes in water and beverage intake and long-term weight changes: results from three prospective cohort studies. Int J Obes (Lond). Oct 2013;37(10):1378–85. doi:10.1038/ijo.2012.225 23318721
70 Pereira MA, Jacobs DR, Jr., Van Horn L, Slattery ML, Kartashov AI, Ludwig DS. Dairy consumption, obesity, and the insulin resistance syndrome in young adults: the CARDIA Study. Jama. Apr 24 2002;287(16):2081–9. doi:10.1001/jama.287.16.2081 11966382
71 Rautiainen S, Wang L, Lee IM, Manson JE, Buring JE, Sesso HD. Dairy consumption in association with weight change and risk of becoming overweight or obese in middle-aged and older women: a prospective cohort study. Am J Clin Nutr. Apr 2016;103(4):979–88. doi:10.3945/ajcn.115.118406 26912496
72 Romaguera D, Angquist L, Du H, Food composition of the diet in relation to changes in waist circumference adjusted for body mass index. PLoS One. 2011;6(8):e23384. doi:10.1371/journal.pone.0023384 21858094
73 Rosell M, Håkansson NN, Wolk A. Association between dairy food consumption and weight change over 9 y in 19,352 perimenopausal women. Am J Clin Nutr. Dec 2006;84(6):1481–8. doi:10.1093/ajcn/84.6.1481 17158433
74 Shin H, Yoon YS, Lee Y, Kim CI, Oh SW. Dairy product intake is inversely associated with metabolic syndrome in Korean adults: Anseong and Ansan cohort of the Korean Genome and Epidemiology Study. J Korean Med Sci. Oct 2013;28(10):1482–8. doi:10.3346/jkms.2013.28.10.1482 24133353
75 Smith JD, Hou T, Ludwig DS, Changes in intake of protein foods, carbohydrate amount and quality, and long-term weight change: results from 3 prospective cohorts. Am J Clin Nutr. Jun 2015;101(6):1216–24. doi:10.3945/ajcn.114.100867 25854882
76 Snijder MB, van Dam RM, Stehouwer CD, Hiddink GJ, Heine RJ, Dekker JM. A prospective study of dairy consumption in relation to changes in metabolic risk factors: the Hoorn Study. Obesity (Silver Spring). Mar 2008;16(3):706–9. doi:10.1038/oby.2007.93 18239556
77 Trichia E, Luben R, Khaw KT, Wareham NJ, Imamura F, Forouhi NG. The associations of longitudinal changes in consumption of total and types of dairy products and markers of metabolic risk and adiposity: findings from the European Investigation into Cancer and Nutrition (EPIC)-Norfolk study, United Kingdom. Am J Clin Nutr. May 1 2020;111(5):1018–1026. doi:10.1093/ajcn/nqz335 31915813
78 Vergnaud AC, Peneau S, Chat-Yung S, Dairy consumption and 6-y changes in body weight and waist circumference in middle-aged French adults. Am J Clin Nutr. Nov 2008;88(5):1248–55. doi:10.3945/ajcn.2007.25151 18996859
79 Wang H, Troy LM, Rogers GT, Longitudinal association between dairy consumption and changes of body weight and waist circumference: the Framingham Heart Study. Int J Obes (Lond). Feb 2014;38(2):299–305. doi:10.1038/ijo.2013.78 23736371
80 Vimaleswaran KS, Zhou A, Cavadino A, Hypponen E. Evidence for a causal association between milk intake and cardiometabolic disease outcomes using a two-sample Mendelian Randomization analysis in up to 1,904,220 individuals. Int J Obes (Lond). Aug 2021;45(8):1751–1762. doi:10.1038/s41366-021-00841-2 34024907
81 Yang Q, Lin SL, Au Yeung SL, Genetically predicted milk consumption and bone health, ischemic heart disease and type 2 diabetes: a Mendelian randomization study. Eur J Clin Nutr. Aug 2017;71(8):1008–1012. doi:10.1038/ejcn.2017.8 28225053
82 Chiang K- M, Pan W- H. Causal link between milk consumption and obesity? A 10-year longitudinal study and a Mendelian randomization study. Food & Nutrition Research. 2021;65doi:10.29219/fnr.v65.6300
83 Bergholdt HK, Nordestgaard BG, Ellervik C. Milk intake is not associated with low risk of diabetes or overweight-obesity: a Mendelian randomization study in 97,811 Danish individuals. Am J Clin Nutr. Aug 2015;102(2):487–96. doi:10.3945/ajcn.114.105049 26156736
84 Olafsdottir AS, Skuladottir GV, Thorsdottir I, Hauksson A, Steingrimsdottir L. Maternal diet in early and late pregnancy in relation to weight gain. Int J Obes (Lond). Mar 2006;30(3):492–9. doi:10.1038/sj.ijo.0803184 16331301
85 Guilloty NI, Soto R, Anzalota L, Rosario Z, Cordero JF, Palacios C. Diet, Pre-pregnancy BMI, and Gestational Weight Gain in Puerto Rican Women. Matern Child Health J. Nov 2015;19(11):2453–61. doi:10.1007/s10995-015-1764-4 26100133