# Summary of conclusion statements and grades

The Committee answered the systematic review question, “What is the relationship between dairy milk and milk alternative consumption and growth, body composition, and risk of obesity?”, with the following conclusion statements.^*^ The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

### Children and adolescents

[underlined: Total milk] consumption by younger children may be associated with favorable growth and body composition, and lower risk of obesity during childhood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

A conclusion statement cannot be drawn about the relationship between [underlined: total milk] consumption by older children and adolescents and growth, body composition, and risk of obesity because of substantial concerns with directness, consistency, and risk of bias in the body of evidence. (Grade: Grade Not Assignable)

Consumption of [underlined: higher-fat dairy milk compared to lower-fat dairy milk] by younger children may be associated with favorable growth and body composition, and lower risk of obesity during childhood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

A conclusion statement cannot be drawn about the relationship between consumption of [underlined: milk with different fat content] by older children and adolescents and growth, body composition, and risk of obesity because of substantial concerns with consistency, quantity, and risk of bias in the body of evidence. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between consumption of [underlined: sweetened milk] by younger children and growth, body composition, and risk of obesity because there is no evidence available. (Grade: Grade Not Assignable)

There may not be a relationship between consumption of [underlined: sweetened milk] by older children and adolescents and growth, body composition, and risk of obesity. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

A conclusion statement cannot be drawn about the relationship between consumption of [underlined: milk alternatives] by children and adolescents and growth, body composition, and risk of obesity because there is not enough evidence available. (Grade: Grade Not Assignable)

### Adults and older adults

[underlined: Total milk] consumption by adults and older adults is not associated with measures of body composition or risk of obesity. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

A conclusion statement cannot be drawn about the relationship between consumption of [underlined: milk with different fat] content by adults and older adults and body composition and risk of obesity because of substantial concerns with directness, consistency, and an absence of trial data in the body of evidence. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between consumption of [underlined: sweetened milk] by adults and older adults and body composition and risk of obesity because there is no evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between consumption of [underlined: milk alternatives] by adults and older adults and body composition and risk of obesity because there is not enough evidence available. (Grade: Grade Not Assignable)

### Individuals during pregnancy and postpartum

A conclusion statement cannot be drawn about the relationship between [underlined: milk] consumption during pregnancy and adequacy of gestational weight gain because there is not enough evidence available. (Grade: Grade Not Assignable)

A conclusion statement cannot be drawn about the relationship between [underlined: milk] consumption during postpartum and postpartum weight change because there is no evidence available. (Grade: Grade Not Assignable)

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on consumption of dairy milk and milk alternatives and growth, body composition, and risk of obesity.

1. Measure milk intake with more accuracy and precision, including use of tools that specify type and amount of dairy milk and milk alternatives consistently. Use comparable units for measurement and serving size when appropriate across age groups.
  a. When possible, rather than combining all types of dairy milk and milk alternatives into one category, categorizing intake by dairy milk or milk alternatives and then by fat and sweetened/flavored groupings will enhance accuracy and precision.
2. Conduct longitudinal studies, particularly RCTs, examining sweetened/flavored milk independently.
3. Conduct longitudinal studies, particularly RCTS, examining milk alternatives independently.
4. Examine these relationships further in racial and ethnic minority groups, who are underrepresented in this body of evidence.
5. Consider the impact of lactose intolerance when studying dairy milk, in particular.
6. Parse apart the impact of dairy milk and milk alternative intake across childhood and adolescence, particularly how the relationship between milk fat content and the outcomes of growth, body composition, and risk of obesity may vary across those developmental years.

Table 15 Evidence examining the relationship between dairy milk and milk alternative consumption by children and adolescents and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Confounding and Study Limitations
Randomized controlled trials
Arnberg, 2012^1^; RCT-Parallel, Denmark; Baseline N=203, Analytic N=173 (Attrition: 15%); Power: Power: recruit 200, 10% dropout expected, for diff of 0.4 SD or 1kg, α=0.05, β=80%; Participant characteristics at baseline:; Adolescents with overweight; - Age: Mean (SD): 13.2 (0.7)y; Range: 12–15y; - Female: 62%; - Race/ethnicity: Caucasian: 95%; - SEP: NR; - Anthropometry: BMI, ≤25 kg/m2: 9.8%, 25.1–29.9: 78.8%, ≥30: 11.4%; - Physical activity: NR (instructed to maintain usual level); - Smoking: Non-smoker: 100%; - Diet quality: NR; - TEI: Mean~7525 kJ/d (~1799 kcal/d); Study beverage intake at baseline: Habitual milk/yogurt intake ≤250 mL/d at baseline; Inclusion: Age 12–15y at baseline, habitual milk and yogurt intake ≤250 mL/d, BMI equivalent of adult >25 kg/m2.; Exclusion: smoking, antibiotics in last month, chronic disease | Intervention: Skim milk; Participants were randomized to 1 of 4 groups: the water group, the skimmed milk group, the casein group or the whey group drinking 1 L per day for 12 weeks of the corresponding test drink.; Study purpose: to test whether milk and milk proteins reduce body weight, waist circumference, homeostatic model assessment, plasma insulin, and insulin secretion in adolescents with overweight; Other interventions: N/A; Comparator: Water; Duration: 12wk; Compliance: Percentage of planned intake actually consumed: skim milk 92%, water 95%; Outcomes and assessment methods:; Weight recorded in morning, after overnight fast on digital scale; Height measured in triplicate; Waist circumference at umbilicus level measured in triplicate; BMI-for-age (BAZ), gender and age-specific Z-scores, calculated using WHO software; Baseline, 12wk follow up | [underlined: Waist circumference, cm], Mean (SD), Linear regression; Over time, within group: 0wk, 12wk; Water: 85.3 (6.2), 86.0 (6.7); P=NS; Skim milk: 84.7 (7.7), 87.6 (8.6), P=0.001; Change over time, between groups:; Water: 0.7 (3.7); Skim milk: 2.2 (4.2), P=NS; [underlined: Waist to height ratio], Mean (SD), Linear regression; Over time, within group: 0wk, 12wk; Water: 0.52 (0.04), 0.53 (0.04), P=NS; Skim milk: 0.52 (0.04), 0.54 (0.05), <0.05; Change over time, between groups:; Water: 0.00 (0.02); Skim milk: 0.01 (0.03), P=NS; [underlined: BMI z-score], Linear regression; Change over time, within group:; Water: P=NS, data NR; Skim milk: P=0.008, data NR; Change over time, between groups: Skim milk > Water, P<0.05, data NR; BMI, kg/m^2^, Mean (SD), Linear regression Over time, within group: 0wk, 12wk; Water: 25.2 (2.3), 25.5 (2.4); P<0.010; Skim milk: 24.9 (2.5), 25.8 (2.8); P<0.001; Change over time, between groups:; Water: 0.3 (0.8); Skim milk: 0.6 (0.9), P<0.022; [underlined: Weight], Linear regression; Change over time, within group:; Water: P<0.001, data NR; Skim milk: P<0.001, data NR; Change over time, between groups:; Skim milk > Water, P=0.032, data NR | Model adjustments:; - TEI: no; - Other:; Limitations:; - Trial registry does not include data analysis plan; Funding:; Danish Agency for Science, Technology and Innovation; Danish Dairy Board
Lambourne, 2013^2^; RCT-Parallel, U.S.; Baseline N=136, Analytic N=108 (Attrition: 21%); Power: Achieved sample size gives 80% power to detect medium difference (Glass’s delta = 0.75) in FFM among groups with alpha = 0.05, assuming correlation between repeated measures up to 0.60; Participant characteristics at baseline:; Adolescents; - Age: Mean: ~14y; - Female: 64%; - Race/ethnicity: Minorities: 86%; - SEP: NR; - Anthropometry: BMI percentile Mean, ~85; - Physical activity: Moderate to vigorous physical activity, Mean ~25 min/d; - Smoking: NR; - Diet quality: NR; - TEI: no; Study beverage intake at baseline: Milk: Mean ~0.7 svg/d; Exclude: BMI ≤50th ≥99th percentile, resistance training in past 12mo, >3hr/wk of endurance training, were not weight stable (+-4.5kg) past 3mo, used tobacco or weight-altering products or medications that could affet metabolism, had an eating disorder, depression, psychiatric illness, specialized diet regime, food allergies, or lactose intolerance; calcium intake >1,000 mg/d, milk inake >1.5 8oz serv/d | Intervention: Milk (24 fl oz/d of fat-free chocolate milk and 1% fat white milk; resistance training 3d/wk), n=36 (Boys, n=13; Girls, n=23); Study purpose: to examine the effects of a supervised RT program with daily milk supplementation on weight, fat mass, and fat-free mass in a sample of middle-school students compared to a water control; Other interventions: Resistance training; Comparator: Water (24 fl oz/d bottled water; resistance training 3d/wk), n=38 (Boys, n=12; Girls, n=26); Duration: 6mo; Compliance: Directly observed by study staff on weekdays and obtained by self-report on weekends; Mean (SD) supplements consumed: Milk 83.9% (9.2), Water 89.8% (5.8); Outcomes and assessment methods:; Height and weight measured by trained research staff; BMI percentile calculated using CDC software; Waist circumference measured by trained research staff using procedures of Lohman, Roche, and Martorell (1988); Fat Mass (FM), Fat-free mass (FFM), and; % body fat: assessed via DXA Baseline, 6mo follow up | [underlined: Body mass, kg], Mean (SD), Linear mixed model; [underlined: By study group]: baseline, 6mo change; Water: 62.8 (13.8), 2.3 (2.9); Milk: 63.7 (11.2), 3.4 (3.7); Group, p=0.12; Time, p<0.0001; [underlined: Boys]; Water: 65.1 (13.8), 2.8 (3.3); Milk: 65.7 (9.8), 5.2 (3.9); Group, p=0.14; Time, p<0.0001; [underlined: Girls]; Water: 61.8 (14.0), 2.0 (2.8); Milk: 62.7 (12.0), 2.3 (3.2); Group, p=0.60; Time, p<0.0001; [underlined: Fat mass, kg], Mean (SD), Linear mixed model; [underlined: By study group]: baseline, 6mo change; Water: 20.9 (10.2), 0.4 (3.6); Milk: 20.8 (8.1), 1.1 (2.8); Group, p=0.33; Time, p<0.0001; [underlined: Boys]; Water: 17.4 (10.6), −1.9 (4.7); Milk: 17.5 (7.2), 1.3 (2.9); Group, p=0.04; Time, p=0.06; Pairwise comparison, p=0.054; Per protocol analysis, p=NS; [underlined: Girls]; Water: 22.5 (9.8), 1.5 (2.5); Milk: 22.6 (8.2), 1.0 (2.8); Group, p=0.85; Time, p<0.0001; [underlined: Fat free mass, kg], Mean (SD), Linear mixed model; [underlined: By study group]: baseline, 6mo change; Water: 41.4 (8.6), 1.7 (2.9); Milk: 42.3 (7.3), 2.2 (1.9); Group, p=0.06; Time, p<0.0001; [underlined: Boys]; Water: 47.9 (9.7), 4.3 (1.4); Milk: 47.7 (7.4), 3.9 (1.6); Group, p=0.99; Time, p<0.0001; [underlined: Girls]; Water: 38.4 (9.7), 0.5 (1.3); Milk: 39.3 (5.3), 1.2 (1.5); Group, p=0.25; Time, p=0.49; [underlined: Percent fat, %], Mean (SD), Linear mixed model; [underlined: By study group]: baseline, 6mo change; Water: 33.5 (11.0), 0 (3.5); Milk: 33.9 (9.6), −0.2 (3.3); Group, p=0.99; Time, p=0.05; [underlined: Boys]; Water: 25.6 (11.0), −2.8 (3.2); Milk: 27.4 (9.6), −0.2 (3.3); Group, p=0.05; Time, p=0.87; Pairwise comparison, p=0.059; [underlined: Girls]; Water: 37.2 (11.0), 1.3 (2.9); Milk: 37.5 (7.7), −0.1 (3.3); Group, p=0.22; Time, p=0.01; [underlined: WC, cm], Mean (SD), Linear mixed model; [underlined: By study group]: baseline, 6mo change; Water: 77.3 (9.3), 0.6 (4.2); Milk: 76.9 (8.9), 1.2 (3.1); Group, p=0.20; Time, p=0.67; [underlined: Boys]; Water: 79.0 (10.3), 0.9 (5.2); Milk: 79.2 (8.1), 2.1 (3.6); Group, p=0.21; Time, p=0.85; [underlined: Girls]; Water: 76.6 (8.9), 0.4 (3.8); Milk: 75.6 (9.2), 0.7 (2.8); Group, p=0.25; Time, p=0.49; [underlined: BMI percentile], Mean (SD), Linear mixed model; [underlined: By study group]: baseline, 6mo change; Water: 84.7 (12.7), 0.3 (7.1); Milk: 83.9 (14.7), 0.9 (7.3); Group, p=0.56; Time, p<0.0001; [underlined: Boys]; Water: 85.6 (12.7), −2.0 (4.5); Milk: 85.4 (14.7), 1.9 (8.9); Group, p=0.07; Time, p=0.04; [underlined: Girls]; Water: 84.3 (12.7), 1.4 (7.9); Milk: 83.0 (15.1), 0.3 (6.3); Group, p=0.94; Time, p<0.0001 | Model adjustments:; - TEI: no; - Other: Study site; Limitations:; - No information on randomization and concealment of allocation sequence; No preregistered data analysis plan; Funding:; Dairy Research Institute
Larnkjær, 2014^3^; RCT-Parallel, Denmark; Baseline N=203, Analytic N=193 (Attrition: 5%); Power: Recruit 200, 10% dropout expected, for diff of 0.4 SD or 1kg, α=0.05, β=80%; Participant characteristics at baseline:; Adolescents with overweight; - Age: Mean (SD): 13y (0.7); - Female: 62%; - Race/ethnicity: Caucasian: 95%; - SEP: NR; - Anthropometry: BMI, ≤25: 9.8%, 25.1–29.9: 78.8%, ≥30: 11.4%; - Physical activity: NR (instructed to maintain usual level); - Smoking: Non-smoker: 100%; - Diet quality: NR; - TEI: ~7,525 kJ/d (~1,799 kcal/d); Study beverage intake at baseline:; Habitual milk/yogurt intake ≤250 mL/d; Include: aged 12–15y, sex- and age-adjusted BMI equivalent of adult BMI >25kg/m2, daily intake of milk and yogurt <250mL; Exclude: chronic illness, antibiotics in past month, smoking | Intervention: Skim milk; Participants were randomized to 1 of 4 groups: the water group, the skimmed milk group, the casein group or the whey group drinking 1 L per day for 12 weeks of the corresponding test drink.; Study purpose: to investigate the effect of milk proteins on linear growth, IGF-I, IGF binding protein-3 (IGFBP-3) and IGF-I/IGFBP-3 ratio in adolescents with overweight; Comparator: Water; Duration: 12wk; Compliance: Percentage of planned intake actually consumed, skim milk 92±11%, water 95±7%; Outcomes and assessment methods:; Height measured in triplicate and averaged to the nearest 0.01 cm.; Age- and sex-specific height z-score calculated using WHO Anthro 2007 Baseline, 12wk follow up | [underlined: Height, cm], Mean (SD), Linear regression; [underlined: Over time, within group]: 0wk, 12wk; Water: 162.93 (7.56), 163.89 (7.53), P<0.001; Skim milk: 162.43 (7.52), 163.79 (7.19), P<0.001; [underlined: Change over time, between groups]:; Water: 0.96 (0.80); Skim milk: 0.92 (0.90) P=NS; [underlined: Height Z-score], Mean (SD), Linear regression; [underlined: Over time, within group]: 0wk, 12wk; Water: 0.86 (0.95), 0.84 (0.94), P=0.084; Skim milk: 0.78 (0.87), 0.79 (0.85), P=0.050; [underlined: Change over time, between groups]:; Water: −0.02 (0.10); Skim milk: −0.03 (0.10) P=NS | Model adjustments:; - TEI: no; - Other:; Limitations:; - Trial registry does not include data analysis plan; Funding:; Danish Agency for Science, Technology and Innovation; Danish Dairy Board
Larnkjær, 2015^4^; RCT-Parallel, Denmark; Baseline N=203, Analytic N=193 (Attrition: 5%); Power: Recruit 200, 10% dropout expected, for diff of 0.4 SD or 1kg, α=0.05, β=80%; Participant characteristics at baseline:; Adolescents with overweight; - Age: Mean (SD): 13y (0.7); - Female: 62%; - Race/ethnicity: Caucasian: 95%; - SEP: NR; - Anthropometry: BMI mean, ~24.8kg/m^2^ BMI, ≤25: 9.8%, 25.1–29.9: 78.8%, ≥30: 11.4%; - Physical activity: Pedometer counts ~9648; (instructed to maintain usual activity); - Smoking: Non-smoker: 100%; - Diet quality: NR; - TEI: ~7,525 kJ/d (~1,799 kcal/d); Study beverage intake at baseline:; Habitual milk/yogurt intake ≤250 mL/d; Include: aged 12–15y, sex- and age-adjusted BMI equivalent of adult BMI >25kg/m2, daily intake of milk and yogurt <250mL; Exclude: chronic illness, antibiotics in past month, smoking | Intervention: Skim milk; Participants were randomized to 1 of 4 groups: the water group, the skimmed milk group, the casein group or the whey group drinking 1 L per day for 12 weeks of the corresponding test drink.; Study purpose: to investigate the effect of milk proteins and water on body composition and leptin in adolescents with overweight; Comparator: Water; Duration: 12wk; Compliance: Percentage of planned intake actually consumed, skim milk 92±11%, water 95±7%; Outcomes and assessment methods:; Total body fat (BF), lean mass, android fat (AF), and gynoid fat (GF) assessed using DEXA; Fat mass index (FMI, fat mass/height2), lean mass index (LMI, lean mass/height2), and percentages of BF, AF, and GF were calculated from DEXA data; Android fat:gynoid fat (AF/GF) ratio was calculated as android fat mass (g)/gynoid fat mass (g); Baseline, 12wk follow up | FMI, kg/m^2^, Mean (SD), Linear regression; Over time, within group: 0wk, 12wk; Water: P=NS, data NR; Skim milk: P<0.05, data NR; Change over time, between groups:; Skim milk > Water, P<0.05, data NR; [underlined: LMI], Mean (SD), Linear regression; Over time, within group: 0wk, 12wk; Water: P<0.05, data NR; Skim milk: P<0.05, data NR; Change over time, between groups: P=NS; [underlined: AF%], Mean (SD), Linear regression; Change over time, within group: 0wk, 12wk; Water: 8.19 (0.73), 8.14 (0.81), P=0.346; Skim milk: 8.23 (0.96), 8.23 (0.90), P=0.646; Change over time, between groups:; Water: −0.05 (0.39); Skim milk: 0.03 (0.43) P=0.265; [underlined: GF%], Mean (SD), Linear regression; Change over time, within group: 0wk, 12wk; Water: 19.2 (1.7), 19.4 (1.8), P=0.112; Skim milk: 19.0 (1.8), 19.0 (1.8), P=0.918; Change over time, between groups:; Water: 0.18 (0.77); Skim milk: −0.07 (0.80) P=0.211; [underlined: AF/GF ratio], Mean (SD), Linear regression; Change over time, within group: 0wk, 12wk; Water: 0.43 (0.06), 0.43 (0.07), P=0.057; Skim milk: 0.44 (0.08), 0.44 (0.08), P=0.656; Change over time, between groups:; Water: −0.01 (0.02); Skim milk: 0.00 (0.02) P=0.095 | Model adjustments:; - TEI: no; - Other:; Limitations:; - Trial registry does not include data analysis plan; Funding:; Danish Agency for Science, Technology and Innovation; Danish Dairy Board
Rahmani, 2011^5^; RCT-Cluster, Iran; Baseline N=469, Analytic N=469 (Attrition: 0%); Power: NR; Participant characteristics at baseline:; Children; - Age: Mean (SD): ~8y (1); (Boys 94.9 (10.7) mo; Girls 90.5 (11.4) mo); - Female: 51%; - Race/ethnicity: NR; - SEP: Schools located in medium SEP region; % of participants with separate room for children in their house:; Intervention: 25%, Control: 21%; - Anthropometry: Baseline weight (kg), mean (SD); Control: 22.6 (4.4), Milk: 23.9 (5); Baseline, between groups: P < 0.05; Girls: Control: 20.9 (3.7), Milk: 23.1 (4.0); Baseline, between groups: P<0.05; Boys: Control: 24.8 (4.1), Milk: 24.6 (5.7); Baseline, between groups: P=NS; - Physical activity: NR; - Smoking: NR; - Diet quality: % reporting never eating breakfast:; Control: 11.9%; Intervention: 8.9%; - TEI: NR; Study beverage intake at baseline: NR; Inclusion/exclusion criteria: NR | Intervention: Milk supplementation (2.5% fat, 250 mL/d), n=235; Study purpose: to evaluate the effects of milk supplementation on physical, mental and school performance of students; Comparator: No milk supplementation, n=234; Duration: 3mo; Compliance: There were no reports of not consuming milk from the intervention schools; Outcomes and assessment methods:; Weight measured using a digital scale Height measured using tape measure Mid-arm circumference measured to nearest 0.1 cm with tape wrapped around arm at mid-point; Baseline, 3mo | [underlined: Weight (kg)], Mean (SD); [underlined: Total]; Baseline, Post-intervention; within group:; Control: 22.6 (4.4), 24.0 (4.0), P<0.05; Milk: 23.9 (5), 24.2 (5). P<0.05; Post-intervention, between groups: P=NS; [underlined: Girls]; Control: 20.9 (3.7), 23 (3.8), P<0.05; Milk: 23.1 (4.0), 23.8 (4.3). P<0.05; Post-intervention, between groups: P<0.05; [underlined: Boys]; Control: 24.8 (4.1), 25.1 (4.2), P<0.05; Milk: 24.6 (5.7), 24.5 (6). P=NS; Post-intervention, between groups: P=NS; [underlined: Height (cm)], Mean (SD); [underlined: Total]; Baseline, Post-intervention; within group:; Control: 122.8 (6.4), 124.5 (6.3), P<0.05; Milk: 122.3 (7.6), 123.7 (7.4), P<0.05; Post-intervention, between groups: P=NS; [underlined: Girls]; Control: 122.2 (6.8), 123.7 (6.8), P<0.05; Milk: 121.0 (6.5), 122.7 (6.5), P<0.05; Post-intervention, between groups: P=NS; [underlined: Boys]; Control: 123.5 (5.7), 125.5 (5.6), P<0.05; Milk: 123.3 (8.3), 124.5 (8.0), P<0.05; Post-intervention, between groups: P=NS; [underlined: Mid-arm circumference (cm)], Mean (SD); [underlined: Total]; Baseline, Post-intervention; within group:; Control: 17.7 (1.7), 17.8 (1.8), P=NS; Milk: 18.2 (1.9), 18.1 (2), P=NS; Post-intervention, between groups: P=NS; [underlined: Girls]; Control: 17.2 (1.4), 17.1 (1.5), P=NS; Milk: 18.5 (1.7), 18.6 (1.8), P=NS; Post-intervention, between groups: P<0.05; [underlined: Boys]; Control: 18.4 (1.9), 18.6 (1.8), P=NS; Milk: 18.6 (2.1), 18.4 (2.1), P=NS; Post-intervention, between groups: P=NS | Model adjustments:; - TEI: no; - Other:; Limitations:; - Methods for randomization and concealment NR; Unclear if outcome assessors were aware of intervention assignment; No power calculation; No preregistered data analysis plan; Funding:; National Nutrition and Food Technology Research Institute, Shaheed Beheshti University of Medical Sciences; Iranian Tetra-pack company; Al-Zahra University
Non-randomized controlled trials
Gomez, 2021^6^; NRCT, U.S.; Baseline N=66, Analytic N=66 (Attrition: 0%); Power: Power for sample size used ranged from 0.78–0.93; significance set at P≤0.05.; Participant characteristics at baseline:; Adolescent girls; - Age: Mean~15.4y (Range 14–17y); - Female: 100%; - Race/ethnicity: Caucasian; - SEP: NR; - Anthropometry: Body weight, kg, mean (SD); MRT: 61.6 (8.5); RT: 61.0 (8.3); CON: 57.3 (5.4); M: 54.9 (8.8); M group weighed less than MRT and RT at baseline, P≤0.05.; Body fat %: ~27.1%; No differences between groups.; - Physical activity: NR at baseline; - Smoking: 0; - Diet quality: NR at baseline; - TEI: NR at baseline; Study beverage intake at baseline:; Habitual milk consumption >3 svg/d; Included: healthy, no physical, health or eating disorders, no current resistance training program, menarche with a normal menstrual cycle, habitual engagement in moderate aerobic physical activity, medical clearance by participant’s physician; Excluded: >3 servings fluid milk/day, consuming >1000 mg calcium/day, metabolic and/or endocrine disorders, known history of bone disease, use of drugs that influence calcium metabolism, smoking, eating disorders, weight change ±10 lbs over last month, use of oral contraceptives | Intervention: Participants (n=66) placed into one of four groups: 1. milk+resistance training (MRT), n=15; 2. Resistance training (RT), n=15; 3. Milk only (M), n=20; control (CON), n=16. M and MRT groups were instructed to substitute 3 8-ounce servings of 1% fluid milk/day while maintaining daily typical milk and dairy consumption; RT and CON groups were instructed to maintain habitual dietary intake. MRT and RT groups participated in a supervised resistance training program; M and CON groups were instructed to maintain normal activity. MRT group was instructed to consume milk in addition to normal caloric intake; M group was instructed to substitute milk for a nondairy source of equal energy, preferably for SSBs.; Study purpose: to determine the independent and additive effects of two interventions (milk and resistance training) on nutrient adequacy, body composition, and bone health in adolescent girls; Other interventions: N/A; Comparator: Control (CON) group RT group, MRT group; Duration: 12 weeks; Compliance: 97% (270 missed servings of milk out of 8820 total servings); Outcomes and assessment methods:; Height: determined to nearest millimeter with wall-mounted stadiometer (without shoes); Weight: measured on electronic scale to nearest 100g; Waist and hip circumference: obtained in duplicate by same investigator; Body composition (percent, body fat, fat mass, lean body mass, and abdominal fat percentage): DXA, performed by blinded investigator; Baseline, 12wk follow up | [underlined: Height (cm)], change between groups over 12wk:; NS (data NR); [underlined: Weight (kg)], change between groups over 12wk:; Milk only group (M): 1.2; CON: 0.0; p-value NR; [underlined: Waist and hip circumference (units NR)]:; NS (data NR); [underlined: Body fat (%)], change between groups over 12wk:; NS (data NR); [underlined: Fat mass (kg)], change between groups over 12wk:; NS (data NR); [underlined: Lean body mass (kg)], change between groups over 12wk:; NS (data NR); [underlined: Abdominal fat (g)], change between groups over 12wk:; Milk groups (M+MRT): 80; Non-milk groups (CON + RT): −7 P<0.05 | [underlined: Model adjustments:]; - TEI: yes; - Key confounders: Sex, race and/or ethnicity, anthropometry at baseline, physical activity; Other:; [underlined: Limitations:]; - Did not account for key confounders: age, SEP, diet quality; - No preregistered data analysis plan; [underlined: Funding:]; National Dairy Council
Ho, 2005^38^; NRCT, Hong Kong; Baseline N=210, Analytic N=199 (Attrition: 5%); Power: NR; Participant characteristics at baseline:; Female adolescents; - Age: Mean (SD): 14.5y (0.6); - Female: 100%; - Race/ethnicity: 100% Chinese; - SEP: NR; - Anthropometry: BMI Mean: 19.4 kg/m^2^; - Physical activity: MET Mean: ~935; - Smoking: 100% non-smokers; - Diet quality: Baseline macro- and micronutrient intake data in paper; - TEI: Mean: ~1,941; Study beverage intake at baseline: NR; Exclude: disease conditions or medications affecting bone mineral density; soy allergy | Intervention: Calcium-fortified soymilk, 375 mL/d; Study purpose: to study the percentage change in bone mineral density and content of the spine and hip region in a 1y follow-up study between calcium-fortified soymilk supplementation and a non-intervention control; Comparator: No-intervention control; Duration: 12mo; Compliance: NR; Outcomes and assessment methods:; Height and weight measured by study personnel; Growth stage defined as non-growing (no gain in height), descending growth (2–4 cm/y), and end-of-growth (<2cm/y) Baseline, 12mo follow up | [underlined: Height, cm], Mean (SD), linear regression At follow-up, between groups:; Control: 159.30 (6.62); Soymilk: 159.00 (5.22) p=0.658; % change over follow-up, between groups:; Control: 0.32 (0.51); Soymilk: 0.30 (0.53) p=0.797; [underlined: Growth stage, %], chi-square; Control: 6.3% descending growth, 67.4% end-of growth, 26.3% non-growing; Soymilk: 4.8% descending growth, 71.2% end-of-growth, 24.0% non-growing p=0.815; [underlined: Weight, kg], Mean (SD), linear regression At follow-up, between groups:; Control: 49.90 (8.71); Soymilk: 50.20 (6.90) p=0.779; % change over follow-up, between groups:; Control: 2.66 (4.94); Soymilk: 3.26 (4.77) p=0.385; BMI, kg/m^2^, Mean (SD), linear regression At follow-up, between groups:; Control: 19.60 (2.69); Soymilk: 19.90 (2.62) p=0.454; % change over follow-up, between groups:; Control: 2.00 (4.88); Soymilk: 2.63 (4.66) p=0.350 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, physical activity; - Other: Medications; Limitations:; - Did not account for key confounders: SEP, diet quality; - No preregistered data analysis plan; Funding:; Vitasoy International Holdings supplied the calcium-fortified soymilk
Prospective cohort studies
Berkey, 2004^8^; PCS, Growing Up Today Study (GUTS), U.S.; Analytic N=11,634; Participant characteristics at baseline:; Children of the Nurses’ Health Study II participants; - Age: Range: 9–14y; - Female: 57%; - Race/ethnicity: White: 95%; - SEP: NR; - Anthropometry: Overweight (>85th percentile CDC BMI charts): boys: 23.2%; girls: 17.5%; Very lean (<10th percentile): boys: 7.2%; girls: 8.6%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Boys, Mean~2290 kcal/d; Girls, Mean~2050 kcal/d; Study beverage intake at baseline: Milk intake (boys): Mean ~2.2 svg/d; Milk intake (girls): Mean ~1.9 svg/d; N/A | Exposure: Dairy milk (serv/d): White milk (in a glass or on cereal) and chocolate milk combined; Other exposures: 100% juice, SSB, LNCSB; Comparator: Continuous milk intake; Assessment methods and timing: Self-administered semi-quantitative, validated FFQ for older children and adolescents; Represents intake during previous year; At baseline, 1y follow-up, 2y follow-up; Outcomes and assessment methods:; BMI from height and weight self-reported by children with measuring instructions and suggestion to ask someone for help provided (all have mothers who are nurses in NHSII); At baseline, 1y, & 2y follow-ups | [underlined: BMI change over 1y], kg/m2, β (SE), Linear regression; Per svg/d change over the same 1y period:; Not adjusted for TEI; Boys: 0.028 (0.015), p=0.054; Girls: 0.019 (0.013), p=0.153; Adjusted for TEI; Boys: 0.016 (0.016), p=0.323; Girls: 0.016 (0.014), p=0.250 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, physical activity; - Other: Tanner stage, menarche (girls), height growth, milk type (whole/2%/1%/nonfat/soy), inactivity, other beverage intake (sugar added, diet soda, fruit juices); Limitations:; - Did not account for key confounders: SEP, diet quality; - Children lost to follow-up were older and had higher sugar added beverage intake and lower milk intake at baseline; self-reported outcome data; no preregistered data analysis plan; Funding:; NIH; Boston Obesity Nutrition Research Center Grant; CDC; Economic Research Service of the USDA; Kellogg’s
Berkey, 2005^9^; PCS, Growing Up Today Study (GUTS), U.S.; Analytic N=13,514; Participant characteristics at baseline:; Children of the Nurses’ Health Study II participants; - Age: Range: 9–14y; - Female: 56%; - Race/ethnicity: White: 95%; - SEP: NR; - Anthropometry: Overweight (85th to 95th percentile CDC BMI charts): boys: 14.6%; girls: 12.7%; Obesity (>95th percentile): boys: 8.7%; girls: 4.8%; Very lean (<5th percentile): boys: 4.2%; girls: 4.7%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Boys, Mean~2290 kcal/d; Girls, Mean~2050 kcal/d; Study beverage intake at baseline: Milk intake (boys): Mean ~2.2 svg/d; Milk intake (girls): Mean ~1.9 svg/d; N/A | Exposure: Dairy milk (serv/d): White milk (in a glass or on cereal) and chocolate milk combined; soymilk was excluded; Comparator: Milk intake, continuous and categorical (>1-≤2; >2-≤3; >3); Assessment methods and timing: Self-administered semi-quantitative, validated FFQ for older children and adolescents; Represents intake during previous year; At baseline, 1y follow-up, 2y follow-up, 3y follow-up; Outcomes and assessment methods:; BMI from height and weight self-reported by children with measuring instructions and suggestion to ask someone for help provided (all have mothers who are nurses in NHSII); At baseline, 1y, 2y, & 3y follow-ups | [underlined: BMI change over 1y Per 1y svg/d change] over the same 1y period, kg/m2, β (SE), Linear regression:; [underlined: Milk intake, continuous]; Boys (n=5961): 0.023, p=0.08; Girls (n=7553): 0.023, p=0.05; [underlined: Milk intake, categorical]; BMI change over 3y, kg/m2, β (SE), Linear regression; N=9166 (children who returned survey all 4 yrs); Boys; >2 and ≤3 svg/d (ref; n=499) vs >3 svg/d (n=129): 0.262, p=0.19; Girls; >2 and ≤3 svg/d (ref; n=652) vs >3 svg/d (n=129): 0.213, p=0.24; [underlined: Incident overweight], RR (95% CI), Logistic regression; N=NR; Between group differences:; Boys; >1 and ≤2 svg/d (ref) vs >3 svg/d: 1.35 (0.96, 1.90); >2 and ≤3 svg/d (ref) vs >3 svg/d: 1.26 (0.95, 1.66); Girls; >1 and ≤2 svg/d (ref) vs >3 svg/d: 1.36 (0.92, 2.01); >2 and ≤3 svg/d (ref) vs >3 svg/d: 1.25 (0.91, 1.72) | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, physical activity; - Other: Prior milk intake, same-year height growth, tanner stage, menstrual history (girls), same-year inactivity (TV/ videos/ computer games); Limitations:; - Did not account for key confounders: SEP, diet quality; - Children lost to follow-up were older and had higher sugar added beverage intake and lower milk intake at baseline; self-reported outcome data; no preregistered data analysis plan; Funding:; NIH; Boston Obesity Nutrition Research Center Grant; CDC; Economic Research Service of the USDA; Kellogg’s; Breast Cancer Research Foundation
Berkey, 2009^7^; PCS, Growing Up Today Study (GUTS), U.S.; Analytic N=5,101; Participant characteristics at baseline: Female children; daughters of Nurses’ Health Study II participants; - Age: Mean: ~11.2y Range: 9–14y; - Female: 100%; - Race/ethnicity: Non-Hispanic White: ~95%; - SEP: NR; - Anthropometry: BMI: ~18.2 kg/m2 Height: ~57.8 in; - Physical activity: NR; - Smoking: NR; - Diet quality: Intake data for dairy, fat, and protein sources provided in paper (Table 1); - TEI: Kcal/d by quartile of white dairy milk intake:; Q1: 1,829; Q2: 1,978; Q3: 2,197; Q4: 2,360; Study beverage intake at baseline: Milk intake (glasses/d): 0-<1: 32.1%; 1: 20.4%; 2–3: 36.6%; >3: 10.9%; Milk intake (glasses/d): Mean ~1.9 Chocolate milk intake (glasses/wk): >1: 20%; Inclusion: Premenarchal at baseline; Exclusion: serious medical condition that could affect growth | Exposure: Dairy milk (serv/d): White milk (in a glass or on cereal) and chocolate milk individually and combined; children reported fat content of the milk they usually drink; soymilk was excluded; Other exposures: N/A; Comparator: <1 serv/d (REF) vs. >3 serv/d; Assessment methods and timing: Self-administered, semi-quantitative, validated FFQ for older children and adolescents; Represents intake during previous year; Baseline, annually for 5y; Outcomes and assessment methods:; Annualized height growth from self-reported heights by children with measuring instructions and suggestion to ask someone for help (all have mothers who are nurses in NHSII); Peak height velocity (PHV) defined as largest annualized height growth; Adult height defined as greatest height attained after onset of menses; Baseline, annually for 5y | White milk intake, categorical; Height growth, in, β, p-value, Linear regression; 1y change in height by preceding white milk intake, between group difference (N=5,070):; Not adjusted for TEI; <1 svg/d (ref) vs >3 svg/d: 0.112, p=0.007; Adjusted for TEI; <1 svg/d (ref) vs >3 svg/d: 0.108, p=0.017; Peak height growth velocity (PHV), in, β, p-value, Linear regression; By baseline white milk intake, between group difference (N=5,022):; Not adjusted for TEI; <1 svg/d (ref) vs >3 svg/d: 0.159, p=0.004; Adjusted for TEI; <1 svg/d (ref) vs >3 svg/d: 0.140, p=0.014; Adult height, in, β, p-value, Linear regression; By baseline white milk intake, between group difference (N=4870):; Not adjusted for TEI; <1 svg/d (ref) vs >3 svg/d: 0.317, p=0.001; Adjusted for TEI; <1 svg/d (ref) vs >3 svg/d: 0.297, p=0.003; Chocolate milk intake, categorical - data NR; Milk intake (white + chocolate), continuous; All adjusted for TEI; Height growth, in, β, p-value, Linear regression; 1y change in height per svg/d increase in preceding milk intake (N=5024):; 0.024, p=0.019; PHV, in, β, p-value, Linear regression Per svg/d increase in baseline milk intake (N=4975):; 0.039, p=0.003; Adult height, in, β, p-value, Linear regression; Per svg/d increase in baseline milk intake (N=4829):; 0.076, p=0.001 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline; - Other: Tanner stage (adult height analyses only), cheese intake, yogurt intake; Limitations:; - Did not account for key confounders: SEP, physical activity, diet quality; - Self-reported outcome data; no preregistered data analysis plan; Funding:; NIH; The Breast Cancer Research Foundation
Blum, 2005^10^; PCS, U.S.; Analytic N=166; Participant characteristics at baseline:; Children; - Age: Mean (SD): 9.3 (1.0); Range: 3rd-5th grade; - Female: 55%; - Race/ethnicity: White: 94%; - SEP: NR; - Anthropometry: BMI z-score, Mean=0.47, SD=1.0; Height, Mean=139.4 cm, SD=7.9; Weight, Mean=35.7 kg, SD=8.1; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Mean=1957.7 kcal/d, SD=575.3; Study beverage intake at baseline: Milk (oz/d): Mean=19.5, SD=12.0; N/A | Exposure: Milk (skim, 1%, 2%, whole, chocolate, milkshakes); Other exposures: 100% juice, SSB, LNCSB; Comparator: Continuous milk intake; Assessment methods and timing: 24-hr recall with two interviews per 24-hr period; parents of random sub-sample called to verify consumption at home; Represents intake during past 24-hr on a school day; Baseline, 2y follow-up; Outcomes and assessment methods: Weight and height measured by study staff; BMI z-score calculated (CDC age and gender specific) from height and weight; Overweight: BMIZ ≥1.0; Normal weight: BMIZ<1.0; Baseline, 2y follow-up | [underlined: Change in Milk intake for Change-in-BMIZ subgroups], oz/d; Mean (SD):; Unadjusted analysis; Within group differences (t-tests):; Normal wt at baseline & 2y, n=99: −3.3 (14.4), P<0.05; Overweight at baseline & 2y, n=48; −3.5 (15.0), NS; Gained wt (Normal wt at baseline; Ovwt at 2y), n= 11: −2.8 (10.1), NS; Lost wt (Ovwt at baseline; Normal wt at 2y), n= 6: −4.3 (10.4), NS; Between group differences (ANOVA): All NS; BMI z-score, Increase per oz/d increase in baseline intake, linear regression:; P=NS, Data: NR | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline; - Other: Baseline beverage intake; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP, physical activity, smoking, diet quality; - Single 24-hr recall used to assess intake; impact of high level of missing data on analyses unclear; no preregistered analysis plan; Funding:; NR
Choi, 2022^11^; PCS, Korean National Health Insurance Service (NHIS), South Korea; Analytic N=26,047; Participant characteristics at baseline:; South Korean children; - Age: 3y; - Female: 49%; - Race/ethnicity: NR; - SEP: Mother’s income level (income-based insurance premiums): 48.8% High (premium categories 14–20), 32% Middle (categories 7–13), 19.2% Low (medical aid and categories 1–6); - Anthropometry: Mean birth weight (kg): <2.5 kg: 5.3%, 2.5–4.0 kg: 91.2%, ≥4.0 kg: 3.5%; - Physical activity: "Sweat-inducing" physical activities for 1h+ per day: 73.9% Yes, 26.1% No; - Smoking: NR; - Diet quality: At age 3: Heavy intake of sweet food: Yes 46.8%, No 53.2%; At age 5: Heavy intake of oily and salty food: Yes 15.7%, No 84.3%; Preferring other drinks over water: Yes 15.1%, No 84.9%; - TEI: NR; Study beverage intake at baseline: Intake of fresh milk per day at 3y: None, 7.4%; < 200 mL, 47.5%; 200–500 mL, 41.7%; 500–1000 mL, 3.3%; ≥1000 mL, 0.2%; Inclusion criteria: confirmed BMI; availability of an identical mother-child health insurance number, and mother’s delivery and child’s birth being in the same year; availability of mother’s BMI and income levels; availability of children’s fourth (at age three) health check-up records and birth data from NHIS database | Exposure: Intake of fresh milk per day (none, <200 mL, 200–500 mL, 500–1000 mL, ≥1000 mL); Other exposures: At age 3: Child’s appetite, # of meals and snacks per day, # of meals with family per week, heavy intake of sweet food (yes/no), food allergy restrictions (yes/no), physical activities for 1+ hour/day (yes/no); At age 5: Comparison of eating speed with family, regular meals and snacks (yes/no), quantity of one meal compared to peers, eating only what one wants (yes/no), heavy intake of oily and/or salty food (yes/no), preferring other drinks over water (yes/no), watching TV or any other monitor for 2+ hours/day (yes/no), physical activities for 1+ hour/day (yes/no); Comparator: Different intake of milk (categorical); Assessment methods and timing: Structured, parent-report questionnaire with nutrition subcategory; At age 3; Outcomes and assessment methods:; Height: measured in upright standing position using a machine with accuracy of up to 0.1 cm; Weight: measured with a machine with accuracy of up to 100g; BMI: calculated from height and weight Obesity cutoff in five-year-old children is a BMI within or above sex- and age-specific 95th percentile (2007 Korean National Growth Charts). Age- and sex-specific percentiles for each measurement calculated using a program according to 2007 Korean National Growth Charts for children and adolescents; At age 5 (mean follow-up ~2y) | [underlined: Risk of obesity at age 5], OR (95% CI) 200–500 mL fresh milk/day (n=10,848): Ref; None (n=1,932): 0.64 (0.49–0.83), P=0.001; <200 mL (n=12,377): 0.89 (0.78–1.01), P=0.08; 500–1000 mL (n=847): 1.50 (1.12–2.02), P=0.007; ≥1000 mL (n=43): 0.48 (0.09–2.63), P=0.398 | Model adjustments:; - TEI: No; - Key confounders: Sex, age, race and/or ethnicity, SEP, diet quality, physical activity; - Other: Model 3: child sex, birth weight, birth weight characterization, developmental screening at 3y, maternal BMI, infant feeding practice, income level, dietary behaviors at age 3 (child’s appetite, # of meals/day, # of snacks/day, # meals with family/week, heavy intake of sweet food, eat restriction due to food allergies) and physical activity at age 3 Model 4: child and family characteristics, dietary behaviors at age 3, dietary behaviors at age 5 (comparison of eating speed with family, regular meals and snacks, quantity of one meal vs. peers, eating only what one wants, heavy intake of oily and salty food, preferring other drinks over water, screen time of 2h+/day), physical activity at age 5; Limitations:; - Did not account for key confounders: anthropometry at baseline; - Exposure not well defined; No info on validity of exposure assessment tool; Exposure data only measured at baseline; No preregistered data analysis plan; Funding:; This research received no external funding
DeBoer, 2015^12^; PCS, Early Childhood Longitudinal Survey-Birth Cohort (ECLS-B), U.S.; Analytic N=7,000; Participant characteristics at baseline:; Children; - Age: Mean: 4y; - Female: 49%; - Race/ethnicity: Asian 10.1%, Black 15.4%, Hispanic 19.7%, Other 11.1%, White 43.7%,; - SEP: High 23.2%, Medium High 19.8%, Medium 19.9%, Medium Low 19.0%, Low 18.1%; - Anthropometry: Normal weight (<85th%): 67.7%, Overweight (>85th-95th%): 16.3%, Obesity (>95th%): 16.0%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: Milk intake (svg/d):; <1: 12%, 1: 16%, 2: 30%, 3: 24%, ≥4: 16%; Milk type normally consumed:; Whole milk: 43%, 2% milk: 40%, 1% milk:; 8%, skim milk: 7%, soy milk 2%; Exclusion: non-milk drinkers | Exposure: Milk (all types of milk from a glass, cup or carton, or with cereal); parents were also asked if their child usually drinks whole milk, 2%, 1%, skim, soy, or other.; Other exposures: N/A; Comparator: Continuous milk intake; Categorical milk intake excluding non-milk drinkers (<1, 1, 2, 3, ≥4); Continuous milk intake by amount of fat content; Assessment methods and timing:; Two questions (amount and type) asked via computer-assisted interview overseen by trained assessor; Represents past 7d Baseline; Outcomes and assessment methods:; Weight and height measured by trained researchers; BMI z-score, HAZ, and WHZ generated via computer program using CDC age and gender specific growth measures; Overweight defined as >85th-95th % BMI z-score; Obesity defined as >95th % BMIZ z-score 1y follow up | Milk intake, continuous: Per svg/d increase in baseline intake; β (SE) linear regression; HAZ: 0.075 (0.0166), p<0.001; Milk intake, categorical: ≤2 svg/d (ref) vs ≥3 svg/d: OR (95% CI), logistic regression HAZ: <1 svg/d (ref) vs 2, 3, or >4 svg/d, data NR, P<0.05; 1 svg/d (ref) vs 2 or >4 svg/d, data NR, P<0.05; vs 3 svg/d, data NR, P=NS; Milk type, continuous: Per increase in fat content of milk normally consumed at baseline; β (SE) linear regression; HAZ: −0.147 (0.030), p<0.001; Milk intake, continuous: Per svg/d increase in baseline intake; β (SE) linear regression; BMI z-score: 0.006 (0.023), p=0.789; WHZ: 0.0224 (0.0189), p=0.240; Milk intake, categorical: ≤2 svg/d (ref) vs ≥3 svg/d: OR (95% CI), logistic regression; Overweight: 1.094 (0.917, 1.306), p=0.3187; Obesity: 1.047 (0.863, 1.269), p=0.6427; Adjusted mean z-scores among milk drinkers based on 4y intake on 5y outcomes: linear regression; BMI z-score: Data NR, P=NS WHZ: Data NR, P=NS; Milk type, continuous: Per increase in fat content of milk normally consumed at baseline; β (SE) linear regression; BMI z-score: −0.139 (0.034), p<0.001; WHZ: −0.145 (0.027), p<0.001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, SEP; - Other: none; Limitations:; - Did not account for key confounders: Anthropometry at baseline, physical activity, diet quality; - Exposure measured at baseline only by an unvalidated measure; no info on missing data; no preregistered data analysis plan; Funding:; NIH
Dong, 2015^36^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), U.K.; Analytic N=4,646; Participant characteristics at baseline:; Children; - Age: Mean: 8y; - Female: 49%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean: 16.2; BMI z-score, Mean: 0.1; - Physical activity: Mean (SD): 22.9 min/d (15.4) (at age 11y); - Smoking: NR; - Diet quality: Mean (SD), g/d; Fruit: 80; Vegetables: 74; Whole grains: 12; - TEI: NR; Study beverage intake at baseline: Full-fat milk (g/d), Mean (SD):; 7y: 133 (182); Low-fat milk (g/d), Mean (SD):; 7y: 125 (167); Inclusion: Complete dietary and anthropometric data at 7y, 10y, and 13y | Exposure: Full-fat milk: full-fat milk, other milk and cream; Low-fat milk: semi-skimmed milk, skimmed milk, Soya milk; Other exposures: 100% juice, SSB, LNCSB; Comparator: Continuous milk intake; Assessment methods and timing: Three-day food diary, child report with help from parent; Represents current intake; Ages 7y, 10y, 13y; Outcomes and assessment methods:; Height and weight measured by study personnel Calculated UK age and sex adjusted BMI z-score to represent adiposity; Excessive weight gain: increase in adiposity over 3y compared to reference group; BMI converted to g for interpretation (assumes 0.01 increase in BMI z-score = 50g); Ages 7y, 10y, 13y | [underlined: Excess weight gain (g) over 3y], per 100 g/d increase (change over 3y) or per 100 g/d intake (average of pre- and post measures for each 3y period), Mean, linear regression; [underlined: Full-fat milk intake], continuous; Change: 65, p<0.01; Average: −40, p<0.10; By sex:; Boys (n=2155); Change: 55, p<0.05; Girls (n=2193); Change: 80, p<0.05; Change from 7–10y: 79, p<0.01; Change from 10–13y: 95, p<0.01; [underlined: Low-fat milk intake], continuous; Change: 40, p<0.05; Average: −40, p<0.10; Boys (n=2155); Change: 19, p=NS; Girls (n=2193); Change: 76, p<0.05; Change from 7–10y: 64, p<0.05; Change from 10–13y: 39, p=NS | Model adjustments:; - TEI: no; - Key confounders: Sex, age, SEP, physical activity; - Other: Pubertal status (Tanner stage); Limitations:; - Did not account for key confounders: Race and/or ethnicity, anthropometry at baseline, diet quality; - No info on missing data; no preregistered data analysis plan; Funding:; NR
Dubois, 2016^13^; PCS, Quebec Newborn Twin Study, Canada; Analytic N=304; Participant characteristics at baseline:; Monozygotic (MZ) twin children; - Age: Mean (SD): 9y (0.6); - Female: 55%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI Mean (SD): 16.5 kg/m2 (2.5); - Physical activity: NR; - Smoking: NR; - Diet quality: Food group intake, kcal/d, % of energy intake; Vegetables: 98, 5%; Fruit & fruit juice: 156, 9%; Whole grain: 86, 5%; Data for other food groups and macronutrients available in paper; - TEI: Kcal/d, Mean (SD): 1,814 (393); Study beverage intake at baseline: Kcal/d, Mean (SD); Milk: 167.04 (128.42); High-fat milk: 25.76 (83.02); Low-fat milk: 141.29 (118.45); Milk and alternatives: 318.72 (154.99); High-fat milk and alternatives: 147.25 (126.10); Low-fat milk and alternatives: 171.47 (125.81); Exclusion: dietary data misreporting (EI:BMR ratios of <0.96 and >2.49) | Exposure: Total milk and alternatives High-fat milk and alternatives; Low-fat milk and alternatives; Total milk; Total high-fat milk; Total low-fat milk; Other exposures: 100% juice, SSB; Comparator: Continuous intake; Assessment methods and timing: 24-hr recall performed by registered dietitians; Represents usual intake Baseline; Outcomes and assessment methods:; Height and weight self-reported except at baseline (measured); Intrapair difference (MZ twins) in BMI Discordant twins defined as ≥2 BMI units between pairs at least once at 9, 12, 13, and/or 14y; Ages 9y, 12y, 13y, 14y | Milk intake, continuous; [underlined: Correlation between intrapair differences in intake at 9y (kcal or % energy) and intrapair differences in BMI in subsequent yrs]; Spearman correlation; [underlined: All]: kcal; % energy; 12y (n=238): 0.13; 0.10; 13y (n=226): 0.10; 0.09; 14y (n=212): 0.12; 0.14; Change 9–14y (n=210): 0.16, p<0.10; 0.13, p<0.05; [underlined: Boys]: kcal; % energy; 12y (n=102): 0.02; −0.01; 13y (n=96): 0.11; 0.09; 14y (n=92): 0.05; 0.10; Change 9–14y (n=92): −0.06; 0.01; [underlined: Girls]: kcal; % energy; 12y (n=136): 0.20, p<0.10; 0.19; 13y (n=130): 0.12; 0.14; 14y (n=120): 0.19; 0.24, p<0.10; Change 9–14y (n=108): 0.37, p<0.05; 0.45, p<0.05; High-fat milk intake, continuous; [underlined: Correlation between intrapair differences in intake at 9y (kcal or % energy) and intrapair differences in BMI in subsequent yrs]; Spearman correlation; [underlined: All]: kcal; % energy; 12y (n=238): 0.06; 0.05; 13y (n=226): −0.08; −0.08; 14y (n=212): 0.06; 0.06; Change 9–14y (n=210): −0.04; −0.03; [underlined: Boys]: kcal; % energy; 12y (n=102): 0.21; 0.21; 13y (n=96): 0.05; 0.05; 14y (n=92): 0.09; 0.10; Change 9–14y (n=92): −0.13; −0.12; [underlined: Girls]: kcal; % energy; 12y (n=136): −0.06; −0.07; 13y (n=130): −0.17; −0.18; 14y (n=120): 0.07; 0.06; Change 9–14y (n=108): 0.05; 0.06; Low-fat milk intake, continuous; [underlined: Correlation between intrapair differences in intake at 9y (kcal or % energy) and intrapair differences in BMI in subsequent yrs]; Spearman correlation; [underlined: All]: kcal; % energy; 12y (n=238): 0.10; 0.10; 13y (n=226): kcal: 0.12; 0.11; 14y (n=212): kcal: 0.12; 0.14; Change 9–14y (n=210): 0.18, p<0.10; 0.24, p<0.05; [underlined: Boys]: kcal; % energy; 12y (n=102): −0.05; −0.08; 13y (n=96): 0.11; 0.05; 14y (n=92): 0.06; 0.07; Change 9–14y (n=92): −0.02; 0.02; [underlined: Girls]: kcal; % energy; 12y (n=136): 0.24, p<0.10; 0.25, p<0.05; 13y (n=130): 0.16; 0.20; 14y (n=120): 0.20; 0.26, p<0.05; Change 9–14y (n=108): 0.35, p<0.05; 0.42, p<0.05; Refer to paper and supplemental data for additional analyses on:; - Milk and alternatives intake; - High-fat milk and alternatives intake; - Low-fat milk and alternatives intake; - Comparison of Dietary Intake (at 9 years) Among Leaner and Heavier Twins From Discordant and Concordant MZ Twin Pairs; - Comparison of Dietary Intake at 9 Years Between Discordant MZ Twins for BMI at 9 Years and Older | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, SEP, diet quality; - Other: None; Limitations:; - Did not account for key confounders: Anthropometry at baseline, physical activity; - No info on missing data; no preregistered data analysis plan; Funding:; Fonds Quebecois de la Recherche sur la Societe et la Culture; Fonds de la Recherche en Sante du Quebec; Social Science and Humanities Research Council of Canada; Nathional Health Research Development Program; CIHR; Sainte-Justine Hospital Research Centre; Academy of Finland
Faith, 2006^14^; PCS, U.S.; Analytic N=825; Participant characteristics at baseline:; Young children; - Age: Mean (SD): 30.2 mo (9.0) Range: 1–5y; - Female: 47%; - Race/ethnicity: Hispanic: 35%, Non-Hispanic Black: 21%, Non-Hispanic White: 36%, Other: 9%; - SEP: Parent education: <High school: 31%, High school: 40%, >High school: 29%; - Anthropometry: At risk for overweight (>85th-94th percentile): 15.6%; Overweight (>95th percentile): 17.3%; - Physical activity: NR; - Smoking: NR; - Diet quality: Serv/d, Mean (SD):; Vegetables (excluding potatoes and carrots): 1.7 (0.9; Fruits (excluding juice): 2.3 (1.0); - TEI: NR; Study beverage intake at baseline: Milk intake: ~3.2 svg/d; Consumes 2% or whole milk: 89.2% (boys), 93.8% (girls); Inclusion: current participation in WIC, aged 1–5y at baseline; Exclusion: missing race/ethnicity data | Exposure: Dairy milk servings/d (defined as 3/4c) and type(s) of milk usually consumed (whole, 2%, 1%, and/or skim); Other exposures: Juice drinks/SSB; Comparator: Continuous intake Assessment methods and timing:; Non-validated parent-report questionnaire of usual daily intake; Baseline; Outcomes and assessment methods:; Weight was measured by WIC staff using a standard balance-beam scale; Height for children >36in tall or >2y measured with stadiometer; otherwise, length was measured using a recumbent board; length converted to height by subtracting 0.5cm; BMI, BMIZ, weight-for-height-Z computed with CDC growth charts; Change in adiposity: defined as change in age- and gender-standardized BMI per month (i.e., BMI z-score slope); Categorical: ≥85th percentile = at risk for overwt or overwt; <85th percentile = not at risk or overwt; Every 6mo for 18–48mo | [underlined: Change in adiposity per month (BMI z-score slope) per serv/d increase], Multivariate linear regression, β (SE); [underlined: Overall milk intake]; Pooled (n=825): −0.002 (0.002), P=0.39; At risk/overwt (n=264): −0.003 (0.003), P=0.31; Not at risk/overwt (n=561): −0.001 (0.002), P=0.81; [underlined: 2% & whole milk]; Pooled (n=825): 0.005 (0.007), P=0.48; At risk/overwt (n=264): 0.012±0.013, P=0.25; Not at risk/overwt (n=561): 0.00 (0.009), P=0.99 | Model adjustments:; - TEI: no; - Key confounders: Sex, race and/or ethnicity, anthropometry at baseline, diet quality; - Other: Food group intake, parental feeding behaviors; Limitations:; - Did not account for key confounders: Age, SEP, physical activity; - Exposure assessment not validated; exposure assessed at baseline only; no info on missing data; no preregistered data analysis plan; Funding:; USDA
Fiorito, 2009^15^; PCS, U.S.; Analytic N=166; Participant characteristics at baseline:; Female children; - Age: Mean: 5y; - Female: 100%; - Race/ethnicity: "Predominantly non-Hispanic white"; - SEP: Family income, averaged $50,000–$75,000; Paternal education, 14.9y (2.7); Maternal education, 14.8y (2.3); - Anthropometry: Mean (SD): BMI for age percentile, 59.3 (26.6); Body fat %, 20.6 (4.3); Overweight 18%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: NR; Include: complete dietary intake and body weight data at ≥4/6 measurement occasions, living with both biological parents, absence of severe food allergies or chronic medical problems affecting food intake, absence of dietary restrictions involving animal products | Exposure: Milk included whole and reduced-fat (plain or flavored) milk and was quantified as that consumed as a beverage; Other exposures: 100% juice, SSB; Comparator: Continuous intake; Assessment methods and timing: Three, 24-hr recalls (2 weekdays, 1 weekend day) within 2- to 3-wk period conducted by trained staff using NDS-R software and reported by mother; represents usual intake; Baseline; Outcomes and assessment methods:; Body fat % estimated by tricep and subscapular skinfold thickness at age 5, 7, 9, and 11y and DXA scans at age 9, 11, 13 and 15; At 7, 9, 11, 13, 15y of age | [underlined: Body fat percentage], β, p-value, linear regression; 7y (N=169): −0.02, p=NS; 9y (N=158): −0.06, p=NS; 11y (N=164): 0.01, p=NS; 13y (N=150): 0.04, p=NS; 15y (N=160): −0.08, p=NS | Model adjustments:; - TEI: no; - Key confounders: Sex; - Other: none; Limitations:; - Did not account for key confounders: Age, race and/or ethnicity, SEP, anthropometry at baseline, physical activity, diet quality; - Possible reporting bias (not all outcome measures reported for each beverage type); no preregistered data analysis plan; Funding:; NIH; The National Dairy Council
Haines, 2007^16^; PCS, U.S.; Analytic N=2,516; Participant characteristics at baseline:; Adolescents; - Age: Mean (SD): Middle school cohort, 12.8 y (0.8); High school cohort, 15.8y (0.8); Middle school cohort = 1/3 of participants; High school = 2/3; - Female: 55%; - Race/ethnicity: Asian: 19.6%, black: 18.9%, Hispanic: 5.8%, Native American: 3.6%, mixed race or other: 3.8%; white: 48.3%; - SEP: Low or low-middle SES, 37%; - Anthropometry: BMI (Mean), Girls 22.4, Boys 22.5; Overweight (>85th percentile), Girls 25.7%, Boys 26.4%; - Physical activity: Moderate and vigorous physical activity, Mean (SD): Girls: 5.8 hr/wk (4.7); Boys: 7.4 hr/wk (4.7); - Smoking: NR; - Diet quality: Fruits and vegetables, serv/d, Mean (SD); Girls: 4.2 (2.9); Boys: 3.8 (2.9); - TEI: Mean (SD), kcal/d:; Girls: 1,994 (1047);; Boys: 2,249 (1,216); Study beverage intake at baseline: Total milk, Girls, Mean (SD): 1.4 svg/d (1.4) Total milk, Boys, Mean (SD): 1.9 svg/d (1.5); Exclude: missing survey at baseline or 5y | Exposure: White milk (skim, 1%, 2%, or whole) and chocolate milk combined; Other exposures: SSB, LNCSB; Comparator: Continuous intake; Assessment methods and timing: 149 item semi-quantitative Youth and; Adolescent FFQ (YAQ); Represents usual intake; Baseline, 5y follow up; Outcomes and assessment methods:; Weight and height self-reported Overweight defined as BMI >85th percentile for age and gender, using Must et al. classification; Baseline, 5y follow up | GIRLS:; Overweight at 5y follow-up, OR (95% CI), linear regression; Baseline intake: 1.11 (0.93, 1.33); Change in intake: Data NR, p=NS; Incident overweight, OR (95% CI), linear regression; Baseline intake: 1.31 (0.99, 1.73); Change in intake: Data NR, p=NS; BOYS:; Overweight at 5y follow-up, OR (95% CI), linear regression; Baseline intake: 0.90 (0.75, 1.07); Change in intake: Data NR, p=NS; Incident overweight, OR (95% CI), linear regression; Baseline intake: 0.77 (0.60, 0.99); Change in intake: Data NR, p<0.05 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, SEP, anthropometry at baseline; - Other: Cohort; Limitations:; - Did not account for key confounders: Physical activity, diet quality; - No info on missing data; self-reported outcome data; no preregistered data analysis plan; Funding:; Maternal and Child Health Bureau (HHS)
Hasnain, 2014^17^; PCS, Framingham Children’s Study, U.S.; Analytic N=98; Participant characteristics at baseline:; Children - 3rd and 4th generation descendents of original Framingham cohort; - Age: 3–5y; - Female: 55%; - Race/ethnicity: Non-Hispanic White: 100%; - SEP: Maternal education >college, ~34%; 100% 2-parent household; - Anthropometry: BMI, Mean ~16.1 kg/m2; - Physical activity: Caltrac counts/hr, Mean: ~10.7; - Smoking: NR; - Diet quality: SSB (oz/d), Median (5th-95th %): 4.0 (0.0, 14.1); - TEI: Mean~1724 kcal/d; Study beverage intake at baseline: Total fluid milk, Median (5th, 95th percentile): 8.8 oz/d (2.2, 15.5); Plain milk, Median (5th, 95th percentile): 6.9 oz/d (1.0, 14.7); Flavored milk, Median (5th, 95th percentile): 0.9 oz/d (0.0, 4.9); Inclusion: At least some dietary data age 3–9y and anthropometry data at 15–17y | Exposure: Total milk (plain and flavored milk, small quantities of soymilk and rice beverages); Other exposures: 100% juice, SSB, LNCSB; Comparator: Categorical intake (tertiles); Assessment methods and timing:; Up to 4 sets of 3-d diet records annually completed by parents (up to age 10y) or children (after age 10y); Represents usual intake; At baseline (3–5y), annually for 12y (age 15–17y); Intake patterns were similar from 3–5y and 6–9y, so these categories were collapsed for analyses.; Outcomes and assessment methods:; Weight, height, waist circumference measured by study personnel; Four skinfolds (triceps, subscapular, suprailiac, abdominal) measured in duplicate following standard protocol Percent body fat measured with DXA scan (end of follow-up only); At baseline (3–5y), annually for 12y (age 15–17y) | Effects of intake (by tertiles) at ages 3–9y on outcomes at end of follow-up (ages 15–17y); linear regression; [underlined: Body fat %], Mean:; T1: 30.0%, T2: Data NR, T3: 22.6%, p=0.0095; [underlined: Sum of 4 skinfolds], mm: Data NR, p=0.0465; [underlined: WC], cm: Data NR, p=0.1318; [underlined: Change in sum of skinfolds by intake tertile]; mixed model; T1 vs T2: p=0.0106; T1 vs T3: p=0.0371; T2 vs T3:, p=0.6859; Effects of intake (by tertiles) at ages 3–9y on outcomes at end of follow-up (ages 15–17y); linear regression; [underlined: BMI], kg/m^2^: Data NR, p=0.0895 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, SEP, anthropometry at baseline, physical activity, diet quality; - Other: Percent of calories from fat, mean TV and video time, other beverages consumed, maternal education, maternal BMI; Limitations:; - Did not account for key confounders: None; - Exposure assessment validity unclear; no preregistered data analysis plan; Funding:; NHLBI; National Dairy Council
Huh, 2010^18^; PCS, Project Viva, U.S.; Analytic N=852; Participant characteristics at baseline:; Children born to Project Viva mothers; - Age: Mean: ~2y; - Female: NR; - Race/ethnicity: 9% Black, 17% Other, 74% White; - SEP: Yearly household income, <$40,000: 10%, $40,000–70,000: 21%, >$70,000: 69%; - Anthropometry: Mean: BMI ~13.5, BMI z-score, ~ −0.19; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Mean: ~1,547 kcal/d; Study beverage intake at baseline: Total milk, Mean (SD): 2.6 (1.2) svg/d Predominant milk type consumed: 53.1% whole milk, 26.5% reduced-fat milk, 20.4% 1%/nonfat milk; Exclude: Incomplete diet or anthropometric data; non-milk drinkers, predominantly formula or nondairy milk drinkers | Exposure: Dairy milk: whole, reduced-fat, or 1%/nonfat milk; Other exposures:; Comparator: Continous intake of total milk and fat-specific milks; Assessment methods and timing: Semi-quantitative child FFQ previously validated in preschool children and completed by mothers; represents usual intake; Baseline; Outcomes and assessment methods:; - Height and weight measured by study personnel; - Sex and age specific BMI z score calculated using US national reference data; - Overweight defined as BMI for age and sex ≥85th percentile; Baseline, 1y follow up | [underlined: BMI z-score], B (95% CI), linear regression:; Whole milk, serv/d: −0.09 (−0.16, −0.01), p=0.02; Reduced-fat milk: −0.08 (−0.17, 0.01), p=0.07; 1%/Non-fat milk: 0.05 (−0.06, 0.16), p=0.39; Total milk: 1.01 (0.76, 1.15), p=NS; [underlined: BMI z-score among normal weight (N=645) at baseline]:; Whole milk, serv/d: −0.05 (−0.13, 0.02), p=0.18; Reduced-fat milk: −0.08 (−0.17, 0.02), p=0.13; 1%/Non-fat milk: 0.00 (−0.14, 0.14), p=0.96; Total milk: −0.05 (−0.10, 0.00), p=NS; [underlined: Incident overweight], OR (95% CI), logistic regression:; Whole milk, serv/d: 1.04 (0.74, 1.44), p=0.84; Reduced-fat milk: 0.91 (0.62, 1.34), p=0.63; 1%/Non-fat milk: 0.95 (0.58, 1.55), p=0.83; Total milk: 1.01 (0.76, 1.15), p=NS | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, SEP, anthropometry at baseline; - Other: Nondairy beverage intake, television viewing, maternal BMI, paternal BMI; Limitations:; - Did not account for key confounders: Physical activity, diet quality; - Exposure measured at baseline only; no preregistered data analysis plan; Funding:; NIH; Rexall Cy Pres Fund
Johnson, 2007^19^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), Children in Focus (CIF) subsample, U.K.; Analytic N=5y & 9y (n=521) 7y & 9y (n=682); Participant characteristics at baseline:; British children born to ALSPAC participants from 04/1991–12/1992.; - Age: Mean (SD) 5.16y (0.05); - Female: NR; - Race/ethnicity: NR; - SEP: Maternal education and paternal class: Data NR; - Anthropometry: Fat mass at 5y, kg, Mean(SD) 8.47(4.98); Weight at 5y, kg, Mean(SD) 19.52 (2.54); Overweight at 5y (≥95th percentile): 15%; - Physical activity: NR; - Smoking: NA; - Diet quality: Dietary energy density, kJ/g at 5y: 8.52 (1.49); - TEI: TEI at 5y, Mean (SD) 6218 (1393) kJ/d; Misreporting of TEI, TEI / Estimated energy requirements (EER) at 5y, Mean (SD): 1.06 (0.24); Study beverage intake at baseline: Milk intake, Median (IQR); 5y: 257 (133–388) g/d;; 7y: 242 (117–376) g/d; Paper contains beverage intake data at 5y and 7y stratified by maternal education; Exclude: Missing data on diet or body composition | Exposure: Milk (all milk consumed as a drink throughout the day and milk added to cereal, tea, coffee, hot chocolate, and milkshakes); Other exposures: SSB, 100% juice, LNCSB; Comparator: Different intake level of milk (continuous, g/d or svg/d); Assessment methods and timing: Parent-report, 3-day unweighed dietary records, previously validated using weighed dietary records; Ages 5y, 7y; Outcomes and assessment methods:; Fat mass (kg): DXA; Fat mass index (FMI):; Fat mass (kg) / Height (m^5.8); log transformed; Height: valid measure by study staff; Weight: valid measure by study staff; Age: 10y | [underlined: Change in fat mass], kg/serving (95% CI), p-value, Linear regression; Change 5y-9y per serving of Milk at 5y (n=362):; −0.51 (−0.86, −0.16), p<0.01; Change 7y-9y per serving of Milk at 7y (n=471):; −0.35 (−0.57, −0.14), p<0.01; [underlined: FMI quintile], Spearmean correlation coefficient; By mean volume of milk consumed (g/d) at age 5y:; Data NR, NS; By mean volume of milk consumed (g/d) at age 7y:; Data NR, NS | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP (maternal education, paternal class), anthropometry at baseline, physical activity, smoking, diet quality; - Other: TV watching, parental BMI, fat intake, fiber intake, EI/EER; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - High attrition/missing data; No information on non-completers; No preregistered data analysis plan; Funding:; U.K. Medical Research Council, the Wellcome Trust, and the University of Bristol
Kral, 2008^20^; PCS, U.S.; Analytic N=49; Participant characteristics at baseline:; Children at either high or low risk of obesity based on maternal prepregnancy BMI; - Age: Mean: ~3y; - Female: 44%; - Race/ethnicity: White: 100%; - SEP: NR; - Anthropometry: BMI z-score, Mean ~ −0.4; WC, Mean ~49.8 cm; - Physical activity: NR; - Smoking: NR; - Diet quality: SSB (oz/d), Mean (SEM); Low risk: 1.8 (1.0); High risk: 2.3 (1.0); - TEI: NR; Study beverage intake at baseline: Milk: Mean ~7.5 oz/d; Include: food records at ages 3, 4, 5, & 6y | Exposure: Milk (all milk and milk-based beverages including chocolate milk, milk with powder/syrup, buttermilk, and milkshakes); Other exposures: 100% juice, SSB, LNCSB; Comparator: Continuous intake; Assessment methods and timing: Three day weighed food and beverage record (2 weekdays, 1 weekend day) recorded by primary caregiver; Represents usual intake; Baseline, 1y & 2y follow ups; Outcomes and assessment methods:; Waist circumference measured in triplicate at the narrowest part of torso by trained anthropometrists; Height and weight measured in triplicate by trained anthropometrists; BMI z-score calculated using CDC growth charts; Baseline, 1y, 2y, & 3y follow ups | [underlined: WC change from 5y – 6y], per change in kcal/d from 3y –5y, B (SE), Linear mixed model:; Outliers excluded; −0.01 (0.004), p=0.04; Outliers included; −0.01, p=0.055; [underlined: BMI z-score change from 5y – 6y], per change in kcal/d from 3y – 5y, B (SE), Linear mixed model:; Data NR, p>0.10 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline; - Other: None; Limitations:; - Did not account for key confounders: SEP, physical activity, diet quality; - No information on non-completers; No preregistered data analysis plan; Funding:; NIH; General Clinical Research Center; Nutrition Center of the Children’s Hospital of Philadelphia
Kunaratnam, 2020^21^; PCS, Secondary analysis of Healthy Beginnings Trial (HBT), Australia; Analytic N=327; Participant characteristics at baseline:; Australian children; - Age: Mean (SD): 2y (0.04); - Female: 50%; - Race/ethnicity: NR; - SEP: Mother’s education: 13.2% high school, 56% technical and further education/diploma, 30.5% university; Mother’s income, AUD$: 21.1% <$40,000, 31.4% $40,000 to <80,000, 47.5% ≥$80,000; Mother’s employment: 17.3% unemployed, 64.8% employed, 17.9% other; Mother’s marital status: 93.8% married/de facto, 6.2% single/divorced/widowed; - Anthropometry: 85.9% not overweight, 10.4% overweight, 3.7% obesity; - Physical activity: Outdoor playtime, Mean (SD): 2.22 (1.21) hr/d; - Smoking: N/A; - Diet quality: Daily svgs (Mean): Fruit 2.16, Vegetables 1.84, Salty Snacks 0.70, Sweet Snacks 4.08; Table 2 in paper has additional data; - TEI: NR; Study beverage intake at baseline: Cups (250 mL)/d, Mean (SD): 2.04 (1.21); Inclusion: first-time English-speaking mothers (aged 16y and older) living in southwestern Sydney recruited at 26–36 weeks gestation; mothers were included in analysis if they had children with dietary and lifestyle data at all 3 times points (2, 3.5, and 5y); Exclusion: women with severe medical conditions based on advice given by their doctors; inability to provide informed consent; those with known major fetal anomalies; presence of physical or intellectual disability in a child which is likely to influence physical activity or food habits; presence of chronic health problem in a child likely to influence weight or height; inability of parents or carers to communicate in English | Exposure: Milk intake; no information on milk fat % or sweetener; Other exposures: SSB; Comparator: Different intake of milk (continuous, cups/d); Assessment methods and timing:; Semi-quantitative 17-item FFQ validated for use with preschoolers; mothers were asked to report their child’s quantity of cups of milk/d (250 mL/cup); At 2y, 3.5y and 5y; Outcomes and assessment methods:; Height and weight: valid measure by study staff; BMI: calculated from height and weight. BMI categories defined as "healthy weight" or "overweight/obesity" using IOTF age- and sex-specific BMI cutoffs.; At 3.5y and 5y of age | [underlined: Incidence of overweight/obesity], β (95% CI); At 3.5y based on milk intake at 2y: NS (data not shown); At 5y based on milk intake at 3.5y: NS (data not shown) | Model adjustments:; - TEI: no; - Key confounders: Sex, age,SEP, anthropometry at baseline, diet quality; - Other: maternal age, maternal BMI, child dietary intake, screen time; Paper is unclear: may have also adjusted for language spoken at home, country of birth, total number of children in the family, parity, breastfeeding duration, age of introduction of solids, maternal smoking status, and childcare attendance; Limitations:; - Did not account for key confounders: race and/or ethnicity, physical activity; - Single measure of exposure used in analysis; High and differential attrition/missing data; No preregistered data analysis plan; Limited generalizability; Funding:; Australian National Health and Medical Research Council
Laurson, 2008^22^; PCS, U.S.; Analytic N=268; Participant characteristics at baseline:; Children; - Age: Mean: 11y; - Female: 46%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean: ~19.0 kg/m2; Normal weight: 74%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: Milk intake at baseline, Mean (SD): Boys 10.5 (4.4), Girls 9.3 (4.6); Exclude: incomplete data | Exposure: Milk (no further specification given); Other exposures: SSB; Comparator: Continuous intake; Assessment methods and timing: Unvalidated questionnaire, how often they consumed milk (per week); represents usual intake; Baseline, 18mo follow up; Outcomes and assessment methods:; Height and weight measured using standard procedures; details NR; BMI calculated weight in kg divided by height in meters squared; Normal weight (BMI-for-age<85th%); Non-obesity (BMI-for-age<95th%); Baseline, 18mo follow up | [underlined: BMI, 18-mo change] based on baseline milk intake, Linear regression, β (SE):; [underlined: Boys]: Change per svg/wk increase:; Overall sample: 0.006 (0.027), P=0.942; Normal weight: 0.016 (0.029), P=0.881; Non-obesity: 0.020 (0.027), P=0.830; [underlined: Girls]: Change per svg/wk increase:; Overall sample: 0.117 (0.027), P=0.213; Normal weight: 0.017 (0.025), P=0.869; Non-obesity: 0.147 (0.027), P=0.131; [underlined: BMI, 18-mo change] based on change in milk intake, Linear regression, β (SE):; [underlined: Boys]: Change per svg/wk increase:; Overall sample: 0.129 (0.26), P=0.168; Normal weight: 0.052 (0.029), P=0.671; Non-obesity: 0.076 (0.025), P=0.454; [underlined: Girls]: Change per svg/wk increase:; Overall sample: 0.071 (0.031), P=0.500; Normal weight: 0.166 (0.032), P=0.180; Non-obesity: 0.135 (0.033), P=0.234 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline; - Other: State of residence (rural Idaho, Montana, or Wyoming); Limitations:; - Did not account for key confounders: SEP, physical activity, diet quality; - Unvalidated exposure measure with high risk of misclassification; No preregistered data analysis plan; Funding:; USDA
Lin, 2012^23^; PCS, “Children of 1997” Birth Cohort, Hong Kong; Analytic N=3,622; Participant characteristics at baseline:; Adolescents; - Age: Mean: 11y; - Female: 51%; - Race/ethnicity: Mother’s birthplace: Mainland China or elsewhere: 37%, Hong Kong: 63%; - SEP: Highest parental education: ≤Grade 9 28%, Grade 10–11 43%, ≥Grade 12 29%; - Anthropometry: BMIZ, Mean: ~0.24; - Physical activity: <1 hr/d: 71%, ≥1 hr/d: 29%; - Smoking: NR; - Diet quality: Intake frequency past week Vegetables: None: 2%; 1–3x: 9%; 4–6x: 12%; Daily: 77%; Fruit: None: 4%; 1–3x 27%; 4–6x: 18%; Daily: 51%; - TEI: NR; Study beverage intake at baseline: Milk intake (times/wk): None 34%, 1–3 34%, 4–6 10%, Daily 22%; Exclusion: N/A | Exposure: Cow’s milk and milk powder; Other exposures:; Comparator: Categorical intake (None, 1– 3 d/wk, 4–6 d/wk, Daily); Assessment methods and timing: Validated FFQ; represents usual intake; Baseline; Outcomes and assessment methods:; Weight and height measured through annual check-ups from Dept of Health-Student Health Services using undisclosed methods; Age- and sex-specific BMI z-scores (BMIZ) calculated based on 2007 WHO growth standard; Baseline, 1.5y follow up | [underlined: BMIZ], mean difference in BMIZ at 13y per milk intake at 11y; Linear regression, β (95% CI); With multiple imputation None (ref, n=2067); 1–3 times/wk (n=2110): 0.003 (−0.04, 0.05); 4–6 times/wk (n=555): −0.01 (−0.08, 0.06); Daily (n=1236): −0.01 (−0.07, 0.05); P for trend=0.655; Available case analysis (no imputation) None (ref, n=1003); 1–3 times (n=997): −0.02 (−0.07, 0.04); 4–6 times (n=282): −0.05 (−0.14, 0.03); Daily (n=615): −0.05 (−0.12, 0.03); P for trend=0.128 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, SEP, anthropometry at baseline, physical activity, diet quality; - Other: Birth order, maternal age, maternal birthplace, birth weight, breastfeeding, pubertal stage, other food consumption (fish, seafood, meat, soy milk, tea, water, etc.); Limitations:; - Did not account for key confounders: None; - Exposure at baseline only and assessed intake frequency only, not amount; no preregistered data analysis plan; Funding:; Government of Hong Kong; Government of the Hong Kong SAR; University of Hong Kong
Marabujo, 2018^24^; PCS, Epidemiological Health Investigation of Teenagers (EPITeen), Portugal Analytic N=941; Participant characteristics at baseline:; Adolescents; - Age: Mean: 13y; - Female: 53%; - Race/ethnicity: NR; - SEP: Parents maximum education level: 1–4th grade 10%, 5–6th grade 9%, 7–9th grade 17%, 10–11th grade 13%, 12th grade 19%, College 33%; - Anthropometry: Underweight/normal weight 76%, Overweight 15%, Obesity 9%; - Physical activity: Extracurricular activity ≥20 min duration: Never 17%, <1/wk 10%, 1/wk 12%, 2–3/wk 35%, 4–6/wk 12%, Almost daily 15%; - Smoking: NR; - Diet quality: NR; - TEI: Mean: 2,438 kcal/d; Study beverage intake at baseline: Milk intake at baseline: Mean~406 g/d Frequency of milk intake at baseline (cups/d): ≤1: 56%; 2–3: 36%; >3: 8%; Exclude: missing data on variables of interest, outliers for energy intake or fruit/vegetable intake | Exposure: Dairy milk intake (sum of skim, semi-skimmed, and full fat milks); Other exposures:; Comparator: Continuous intake; Categorical intake (≤1, 2–3, >3 cups/d); Assessment methods and timing: Validated FFQ; represents usual dietary intake in previous 12 months; Baseline, 8y follow up; Outcomes and assessment methods:; Height measured by trained health professionals using stadiometer; Weight measured by trained health professionals using digital scale; BMI calculated as weight in kg divided by height in meters squared; Baseline, 8y follow up | [underlined: BMI at age 21], and milk intake at age 13 (change per 100 g/d increase); Linear regression, β (95% CI); TEI unadj: −0.021 (−0.107, 0.066); TEI adj: −0.018 (−0.106, 0.069); [underlined: BMI at 21y] per milk intake at 13y, ANOVA, Mean (SD); [underlined: Full sample]:; ≤1 cup/d (n=527): 23.0 (4.0); 2–3 cups/d (n=342): 22.6 (3.3); >3 cups/d (n=72): 23.8 (4.4) P=0.05; [underlined: Girls] (n=501):; ≤1 cup/d: 22.6 (3.9); 2–3 cups/d: 22.1 (3.3); >3 cups/d: 24.5 (5.2) P=0.002; [underlined: Boys] (n=440):; ≤1 cup/d: 23.5 (4.0); 2–3 cups/d: 23.2 (3.2); >3 cups/d: 23.0 (3.1) P=0.572 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP, physical activity; - Other: Follow-up period, total calcium intake at follow-up, self-reported diabetes, asthma and eating disorders; Limitations:; - Did not account for key confounders: Race and/or ethnicity, anthropometry at baseline, diet quality; - No information on non-completers; No preregistered data analysis plan; Funding:; FEDER; Foundation for Science and Technology-FCT; Unidade de Investigação em Epidemiologia (EPIUnit)
Marshall, 2018^25^; PCS, Iowa Fluoride and Iowa Bone Development Studies, U.S.; Analytic N=571; Participant characteristics at baseline:; Children; - Age: Range: 2–4.7y; - Female: 51%; - Race/ethnicity: Non-Hispanic white: 94%; - SEP: Mother had 4y college degree: 45%, Household annual income ≥$60,000: 19%; - Anthropometry: Weight, Mean~20.0 kg; Height, Mean~111.4 cm; - Physical activity: NR; - Smoking: NR; - Diet quality: SSB, oz/d, Median (25th, 75th percentile); Males: 2.7 (1.1, 5.1); Females: 2.6 (1.2, 5.1); - TEI: Median~1360 kcal/d; Study beverage intake at baseline: Milk intake at 2–4.7y: Median: 10.9 oz/d; Include: ≥2 assessments ages 2–8.5y or ≥1 ages 9–17y | Exposure: Milk intake (all forms of cow’s milk, including chocolate, low-fat, whole); Other exposures: 100% juice, SSB, LNCSB; Comparator: Continuous intake; Assessment methods and timing: Validated beverage frequency questionnaire; represents previous week’s beverage intakes; At 3- to 6-mo intervals: Agest 2–4.7, 5–8.5, 9–10.5, 11–12.5, 13–14.5, and 15–17y; Intake averaged across all time points for analysis; Outcomes and assessment methods:; Height measured without shoes using stadiometer during clinic visits; At ages 5, 9, 11, 13, 15, 17y | [underlined: Height through age 17y], cm, Change per 8 oz/d increase (intake averaged across all time points); Linear regression:; B: 0.39, 95% CI: 0.18, 0.60, P<0.001 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP, anthropometry at baseline; - Other: Protein intake; Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity, diet quality; - No information on non-completers; No preregistered data analysis plan; Funding:; NIH; The Roy J. Carver Charitable Trust; Delta Dental of Iowa Foundation
Marshall, 2019^26^; PCS, Iowa Fluoride and Iowa Bone Development Studies, U.S.; Analytic N=623; Participant characteristics at baseline:; Children; - Age: Range: 2–4.7y; - Female: 51%; - Race/ethnicity: Non-Hispanic white: 94%; - SEP: Mother had 4y college degree 45%; Household annual income ≥$60,000 19%; Low 25%, Middle 38%, High 38%; - Anthropometry: BMI, Mean~16.0 kg/m2; BMIZ, Mean~0.31; - Physical activity: NR; - Smoking: NR; - Diet quality: SSB, oz/d, Median (25th, 75th percentile); Males: 2.7 (1.1, 5.1); Females: 2.6 (1.2, 5.1); - TEI: Median~1360 kcal/d; Study beverage intake at baseline: Milk intake at 2–4.7y: Median: 10.9 oz/d; Include: ≥2 assessments ages 2–8.5y or ≥1 ages 9–17y | Exposure: Milk intake (all forms of cow’s milk, including chocolate, low-fat, whole); Other exposures: 100% juice, SSB, LNCSB; Comparator: Continuous intake; Assessment methods and timing: Validated beverage frequency questionnaire; represents previous week’s beverage intakes; At 3- to 6-mo intervals: Agest 2–4.7, 5–8.5, 9–10.5, 11–12.5, 13–14.5, and 15–17y; Outcomes and assessment methods:; Height measured without shoes using stadiometer during clinic visits; Weight was measured at clinic visit using a standard physician’s scale; BMIs were calculated from weight and height measures (kg/m2); Age- and sex-specific BMI z-scores (BMIZ) calculated 2000 CDC growth charts; At ages 5, 9, 11, 13, 15, 17y | [underlined: BMIZ change] per 8 oz/d increase in milk (intake averaged across all time points), Linear regression:; B: 0.022, 95% CI: −0.007, 0.052, P=0.13 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP, anthropometry at baseline; - Other: Protein intake, other beverage intake; Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity, diet quality; - No information on non-completers; No preregistered data analysis plan; Funding:; NIH; The Roy J. Carver Charitable Trust; Delta Dental of Iowa Foundation
McGovern, 2022^35^; PCS, Project Viva, U.S.; Analytic N=796; Participant characteristics at baseline:; Young children; - Age: Mean (SD): 3.2 (0.2) y; - Female: 51%; - Race/ethnicity: Black: 12.7%, Other: 18%, White: 69.3%; - SEP: 94% married or cohabitating; Maternal college degree 74%, Paternal college degree 70.8%, Median neighborhood household income $58,300 (SD $21,100), Household income >$70,000 65.4%; - Anthropometry: BMIz at age 3, mean (SD): 0.45 (0.99); 26% with BMI ≥85th percentile; - Physical activity: Active play hours/day, mean (SD): 2.9 (1.6)h; - Smoking: Maternal smoking: during pregnacy 9.3%, former 20.4%, never 70.3%; - Diet quality: Modified Youth Healthy Eating Index score, mean (SD): 37.9 (8.4); - TEI: Mean (SD) 1855.6 (518.9) kcal/d; Study beverage intake at baseline: Cow’s milk intake, times/day, mean (SD): 2.3 (1.2); 63% drank whole or 2% milk, 37% drank 1% or skim milk; Excluded participants: without early adolescent outcomes, invalid exposures in early childhood, who do not drink milk, who drank primarily soy milk or "other" milk (e.g., rice milk and chocolate cow’s milk) | Exposure: Cow’s milk intake (frequency of intake and fat content); Other exposures:; Comparator: Categorical by fat content (whole, 2%, 1%, skim); Categorical by frequency (<1x/wk, 1x/wk, 2–4x/wk, nearly daily or daily, 2–4x/d, ≥5x/d); Frequency transformed to continuous variable by reporting average within each category and recoding weekly measures as daily measures (resulting in 2–4x/wk averaged to 3x/wk and recoded as 0.429 times/d); Assessment methods and timing: Semi-quantitative validated FFQ, representing intake over the last month At baseline (mean age 3.2 years); Outcomes and assessment methods:; All outcomes measured by trained research assistant.; Height measured to nerest 0.1 cm using calibrated stadiometer.; Weight measured to nearest 0.1 kg with a calibrated scale.; WC measured to the nearest 0.1 cm above iliac crest while standing.; Subscapular and triceps skinfold thickness measured to neares 0.1 mm using Holtain calipers to calculate sums of subscapular and triceps skinfold thicknesses.; Body fat % measured using foot-to-foot bio-impedance.; Lean, total fat, and trunk fat mass measured using DXA.; BMI, lean mass index, total fat mass index, and trunk fat mass index were calculated.; BMIz derived from 2000 CDC growth charts; overweight or obesity defined as BMI ≥85th% for age and sex.; At follow-up (mean age 13.1y) | Association of higher; [underlined: BMIz in adolescence] based on intake of lower-fat milk in early childhood:; p=0.62; [underlined: BMIz], β (95% CI), multivariable linear regression, adjusted for modified YHEI at age 2 instead of age 3; Whole/2% vs 1%/skim: −0.14 (−0.27, 0.00); [underlined: Fat mass index], lean mass index, trunk fat mass index, body fat %, sum of subscapular and triceps skinfolds, WC 1% or Skim milk (ref) vs Whole or 2% milk: NS (data reported in figure form only); Per time/day: NS (data reported in figure form only); [underlined: WC (cm)], β (95% CI), multivariable linear regression, adjusted for modified YHEI at age 2 instead of age 3; Whole/2% vs 1%/skim: −1.63 (−3.19, −0.08); [underlined: Overweight or obesity during adolescence] according to milk intake during early childhood, OR (95% CI), multivariable logistic regression 1%/Skim (ref) vs Whole/2%: 0.60 (0.38, 0.93); Per time/day: 1.01 (0.83, 1.22) 2%, 1%, or Skim (ref) vs Whole milk: 0.94 (0.60, 1.48) | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, SEP (parental education, marital status, median neighborhood and individual incomes at birth), anthropometry at baseline, physical activity, diet quality; - Other: milk intake frequency (or milk fat content); maternal age; dietary quality during pregnancy; GWG; parity; gestational age at birth; birth weight for gestational age z-score; breastfeeding duration; sleep duration; TV viewing; intakes of SSB, fiber, juice, sucrose, and other dairy; Limitations:; - Did not account for key confounders: N/A; - Exposure data only measured at baseline; No preregistered data analysis plan; Funding:; NIH; NIDDK
Newby, 2004^27^; PCS, U.S.; Analytic N=1,345; Participant characteristics at baseline:; Low-income preschool children; - Age: Mean (SD): 2.9y (0.7); - Female: 50%; - Race/ethnicity: Native American 11%, Other 6%, White 83%; - SEP: Maternal education, Mean~12.6y; Poverty level: <100%: 55%; 100–133%: 22%; >133–185%: 23%; - Anthropometry: BMI, Mean~16.6 kg/m2; At risk of overweight 14%, Overweight 6%; - Physical activity: NR; - Smoking: NR; - Diet quality: Soda intake: Mean~1.2 oz/d; ≥12 oz/d: ~3%; - TEI: Mean~1747 kcal/d; Study beverage intake at baseline: Milk intake at baseline: Mean~19.9 oz/d; ≥24 oz/d: 33%; Exclude: only 1 clinic visit, underweight, implausible energy intake, unreasonable measures for weight or height | Exposure: Milk intake (all types together since majority of children consumed 2% or whole milk); Other exposures: 100% juice, SSB, LNCSB; Comparator: Continuous intake; Categorical intake (<24 oz/d, ≥24 oz/d); Assessment methods and timing: Validated FFQ; represents dietary intake during previous month; At baseline, follow-up 6–12mo later (mean 8.4mo); Outcomes and assessment methods:; Height measured by trained staff using wall-mounted measuring board; Weight measured by trained staff using standard floor-model beam scale; Age- and sex-specific BMI calculated based on 2000 CDC growth charts; At risk of overweight (BMI 85th to <95th%); Overweight (BMI≥95th%); At baseline, follow-up 6–12mo later (mean 8.4mo) | [underlined: Weight], Linear regression; Change per oz/d increase, β (SE):; TEI adj: 0.00 (0.01), P=0.84 <24 oz/d (ref) vs. ≥24 oz/d:; NS, data NR; [underlined: BMI], Linear regression; Change per oz/d increase, β (SE):; TEI adj: −0.00 (0.00), P=0.96 <24 oz/d (ref) vs. ≥24 oz/d:; NS, data NR; Estimates remained similar when TEI was omitted from model. (Data NR) | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, race and/or ethnicity, SEP, anthropometry at baseline, diet quality (other beverages); - Other: Birth weight; Limitations:; - Did not account for key confounders: Physical activity; - No preregistered data analysis plan; Funding:; USDA; NIH Health Harvard Education Program in Cancer Prevention Control; Boston Obesity Nutrition Research Center
Noel, 2011^28^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), U.K.; Analytic N=2,245; Participant characteristics at baseline:; Children; - Age: Mean (SD): 10.6y (0.2); - Female: 55%; - Race/ethnicity: “Limited variability in race/ethnicity”; - SEP: Mother’s educational attainment: CSE/vocational 16%, Ordinary level 36%, Advanced level/degree 48%; - Anthropometry: Body weight, Mean~37.5 kg; Height, Mean~144 cm; Body fat, Mean~25.5%; - Physical activity: Mean: ~588 counts/min; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: Total milk intake (svg/d), Mean (SD): Boys 1.04 (0.78), Girls 0.79 (0.67); Full-fat milk intake (svg/d), Mean (SD): Boys 0.36 (0.67), Girls 0.26 (0.52); Reduced-fat milk intake (svg/d), Mean (SD): Boys 0.65 (0.75), Girls 0.50 (0.63); Exclude: incomplete dietary or percent body fat data | Exposure: Milk intake (full-fat, reduced-fat, nonfat, flavored cow’s milk);; Other exposures:; Comparator: Continuous intake Assessment methods and timing:; 3-d dietary record completed by child with parental assistance as needed; represents dietary intake on both weekdays and weekend; Plausible dietary reporters based on previously published age- and sex-specific cutoffs; Baseline, 3y follow up; Outcomes and assessment methods:; Body fat percentage (BF%) determined using DEXA; Height measured using stadiometer Weight measured using scale; BMI calculated; Baseline, 3y follow up | [underlined: Body fat %], β (95% CI), Linear regression; [underlined: Total Milk (plain milk and flavored milk)]; Change at 1y f/u (age 11):; Per 100 g milk consumed:; TEI adj: −0.14 (−0.26, −0.01), P=0.03; TEI unadj: 0.01 (−0.18, 0.20), P=0.89; plausible reporters (n=907): −0.16 (−0.37. 0.06), P=0.16; Per milk svg/d:; TEI adj: −0.34 (−0.64, −0.03), P=0.03; TEI unadj: 0.03 (−0.44, 0.50), P=0.89; plausible reporters (n=907): −0.38 (−0.91, 0.15), P=0.16; Change at 3y f/u (age 13):; Per 100 g milk consumed:; TEI adj: −0.06 (−0.21, 0.09), P=0.45; TEI unadj: 0.03 (−0.22, 0.27), P=0.83; plausible reporters (n=876): −0.20 (−0.43, 0.03), P=0.10; Per milk svg/d:; TEI adj: −0.15 (−0.52, 0.23), P=0.45; TEI unadj: 0.06 (−0.53, 0.65), P=0.83; plausible reporters (n=876): −0.49 (−1.06, 0.09), P=0.10; Plain Milk (full-fat, reduced-fat, nonfat) “Associations between plain milk intake and BF% for all models were similar to those observed with total milk intake (data NR)”; [underlined: Full-fat Milk]; Change at 1y f/u per 100 g milk consumed:; TEI adj: −0.10 (−0.24, 0.05), P=0.19; TEI unadj: −0.03 (−0.18, 0.12), P=0.70; plausible reporters (n=907): −0.04 (−0.32, 0.24), P=0.80; Change at 1y f/u per milk svg/d:; TEI adj: −0.24 (−0.60, 0.12), P=0.19; TEI unadj: −0.07 (−0.44, 0.29), P=0.70; plausible reporters (n=907): −0.09 (−0.77, 0.59), P=0.80; Change at 3y f/u per 100 g milk consumed:; TEI adj: −0.10 (0.28, 0.08), P=0.28; TEI unadj: −0.06 (−0.24, 0.13), P=0.56; plausible reporters (n=876): −0.21 (−0.48, 0.07), P=0.14; Change at 3y f/u per milk svg/d:; TEI adj: −0.24 (−0.69, 0.20), P=0.28; TEI unadj: −0.14 (−0.59, 0.32), P=0.56; plausible reporters (n=876):−0.50 (−1.17, 0.17), P=0.14; [underlined: Reduced−fat Milk]; Change at 1y f/u per 100 g milk consumed:; TEI adj: −0.05 (−0.17, 0.08), P=0.47; TEI unadj: 0.07 (−0.08, 0.22), P=0.36; plausible reporters (n=907): −0.09 (−0.30, 0.13), P=0.44; Change at 1y f/u per milk svg/d:; TEI adj: −0.11 (−0.41, 0.19), P=0.47; TEI unadj: 0.17 (−0.19, 0.54), P=0.36; plausible reporters (n=907): −0.21 (−0.73, 0.32), P=0.44; Change at 3y f/u per 100 g milk consumed:; TEI adj: 0.03 (−0.13, 0.18), P=0.74; TEI unadj: 0.09 (−0.10, 0.28), P=0.34; plausible reporters (n=876): −0.03 (−0.27, 0.20), P=0.78; Change at 3y f/u per milk svg/d:; TEI adj: 0.06 (−0.32, 0.44), P=0.74; TEI unadj: 0.22 (−0.24, 0.68), P=0.34; plausible reporters (n=876): −0.08 (−0.66, 0.50), P=0.78; [underlined: Skim Milk]; Was not examined separately since it was consumed by a small number of children (n=200 at age 10y) | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP, anthropometry at baseline, physical activity, diet quality (total fat, ready-to-eat breakfast cereal, 100% fruit juice, SSB, calcium intake); - Other:; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Baseline n not clear; Did not report all outcomes assessed (height, weight, BMI); No preregistered data analysis plan; Funding:; American Diabetes Association; UK Medical Research Council; Wellcome Trust; University of Bristol; NHLBI; Arthritic Association
Noel, 2013^42^; PCS, Avon Longitudinal Study of Parents and Children (ALSPAC), U.K.; Analytic N=2,270; Participant characteristics at baseline:; Children; - Age: Mean (SD): 10.6y (0.2); - Female: 55%; - Race/ethnicity: “Limited variability in race/ethnicity”; - SEP: Mother’s educational attainment: CSE/vocational 16%, Ordinary level 36%, Advanced level/degree 48%; - Anthropometry: Overweight/obesity: 21%; Body fat %, Mean: ~25.5%; - Physical activity: Mean: ~588 counts/min; - Smoking: NR; - Diet quality: Mean (SE), g/d; Vegetables: 64; Fruit: 75; SSB: 107; - TEI:; Study beverage intake at baseline: Flavored milk: Consumers, n=380 (16.7%), Non-consumers, n= 1890 (83.3%); Frequency of flavored milk intake: 1 svg/d= 50 children (2.2%), >1.5 svg/d: 11 children (0.5%); Flavored milk intake (g/d) of consumers, mean (SE): 142 (102); Exclude: incomplete dietary or physical activity data | Exposure: Flavored milk Other exposures:; Comparator: No flavored milk intake; Assessment methods and timing:; 3-d dietary record completed by child with parental assistance as needed; represents dietary intake on both weekdays and weekend; Plausible dietary reporters based on previously published age- and sex-specific cutoffs; Baseline, 3y follow up; Outcomes and assessment methods:; Body fat determined using DEXA Height measured using stadiometer; Weight measured using scale; BMI percentiles calculated from 2000 CDC growth charts;; Normal weight (BMI 5th to <85th%), Overweight/obesity (BMI≥85th%); At baseline (age 10y), 1y (age 11y), and 3y follow-up (age 13y) | [underlined: Body Fat], Mean (95% CI), Linear regression; [underlined: Normal weight (n=1715)]; Flavored milk consumers vs Non-consumers: −0.70 (−1.57, 0.17) vs −0.98 (−1.71, −0.25), P=0.36 (TEI unadj); TEI adj: P=NS, data NR; [underlined: Normal weight, plausible reporters (n=708)]; Flavored milk consumers vs Non-consumers: −1.35 (−2.77, 0.07) vs −1.33 (−2.54, −0.12), P=0.96 (TEI unadj); TEI adj: P=NS, data NR; [underlined: Overweight/obesity (n=449)]; Flavored milk consumers vs Non-consumers: −0.79 (−2.46, 0.88) vs −2.19 (−3.60, −0.78), P=0.02 (TEI unadj); TEI adj: P <0.05, data NR; [underlined: Overweight/obesity, plausible reporters (n=138)]; Flavored milk consumers vs Non-consumers: −0.16 (−3.84, 3.52) vs −3.43 (−6.45, −0.42), P=0.02 (TEI unadj); TEI adj: P<0.05, data NR; [underlined: Weight], Mean (95% CI), Linear regression; [underlined: Normal weight (n=1715)]; Flavored milk consumers vs Non-consumers: 11.3 (10.7, 12.0) vs 11.1 (10.6, 11.6), P=0.35 (TEI unadj); TEI adj: P=NS, data NR; [underlined: Normal weight, plausible reporters (n=708)]; Flavored milk consumers vs Non-consumers: 11.1 (10.0, 12.1) vs 11.1 (10.3, 12.0), P=0.83 (TEI unadj); TEI adj: P=NS, data NR; [underlined: Overweight/obesity (n=449)]; Flavored milk consumers vs Non-consumers: 12.6 (10.7, 14.4) vs 11.7 (10.1, 13.2), P=0.18 (TEI unadj); TEI adj: P=NS, data NR; [underlined: Overweight/obesity, plausible reporters (n=138)]; Flavored milk consumers vs Non-consumers: 14.5 (11.1, 18.0) vs 11.6 (8.8, 14.4), P=0.02 (TEI unadj); TEI adj: P<0.05, data NR | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP, anthropometry at baseline, physical activity, diet quality (total fat, ready-to-eat cereal, 100% fruit juice, sugar-sweetened beverages, plain milk and fruit and vegetables); - Other: Fiber, pubertal status, maternal BMI, calcium, dieting at age 13y; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Potential risk of misclassification of exposures; No information on missing data; No preregistered data analysis plan; Funding:; American Diabetes Association; UK Medical Research Council; Wellcome Trust; University of Bristol; NHLBI
Sakaki, 2021^29^; PCS, Growing Up Today II (GUTS), U.S.; Analytic N=8,173; Participant characteristics at baseline: children and adolescents; - Age: Mean (SD): ~13.4y (1.81) (Range: 9–16y); - Female: 56%; - Race/ethnicity: >95% non-Hispanic white; - SEP: NR; - Anthropometry: BMI Mean (SD) Boys: 20.3 (3.9); Girls: 20.2 (3.7); - Physical activity: MET-hrs/wk: Mean (SD); Boys: 91.99 (66.02); Girls: 70.35 (52.13); - Smoking: NR; - Diet quality: NR; - TEI: Mean (SD):; Boys: 2324 kcal/d (724);; Girls: 1953 kcal/d (638); Study beverage intake at baseline: Mean (SD): ~1.6 (1.2) servings/day; Low-fat milk: ~61% High-fat milk: ~39%; Consume any milk at least monthly: 95%; Excluded: missing data on age, race, PA, TEI, or beverage intake at baseline or 2y follow up; implausible energy intake or change in daily intake (n=92), or extremely low BMI (<12kg/m2) (n=64) | Exposure: White cow milk categorized as low-fat milk (skim & 1%) and high-fat milk (2% and whole) (sweetened and plant-based milk intake was measured but not used in analyses due to low intake and high variability); 1 serving = 8 fl oz.; Other exposures: 100% Juice; Comparator: Intake per day, low fat vs high fat milk; Assessment methods and timing: Child/adolescent semi-quanitative FFQ, validated; Baseline; Outcomes and assessment methods:; Participant self-reported and measured height and weight; 2y & 4y follow up | [underlined: BMI change over 2y], β (SE), p-value, linear regression; [underlined: Total white cow milk]:; Boys: 0.03 (0.02), p=0.23;; Girls: −0.01 (0.02), p=0.72; [underlined: Low-fat milk]:; Boys: 0.03 (0.02), p=0.26;; Girls: −0.001 (0.02), p=0.95; [underlined: High-fat milk]:; Boys: 0.00 (0.03), p=0.99;; Girls: −0.02 (0.02), p=0.50 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline, physical activity; - Other:; Limitations:; - Did not account for key confounders: SEP, diet quality; - Exposure not well defined, Exposure data only measured at baseline; No information on non-completers; BMI was self-reported; No preregistered data analysis plan; Funding:; The Florida Department of Citrus (an executive agency of the state of Florida)
Scharf, 2013 ^39^; PCS, Early Childhood Longitudinal Survey Birth Cohort (ECLS), U.S.; Analytic N=8,100; Participant characteristics at baseline:; Preschool-aged children; - Age: 2y; - Female: 49%; - Race/ethnicity: Asian 10.2%, Black 15.0%, Hispanic 20.5%, Other 11.2%, White 43.1%,; - SEP: High 16.2%, Medium high 17.6%, Medium 18.1%, Medium low 18.3%, Low 21.3%; - Anthropometry: Normal weight 69.9%, Overweight 15.0%, Obesity 15.1%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: • Whole or 2% milk: 86% drank at baseline; - 1% milk: 8.5% drank at baseline; - Skim milk: 2.1% drank at baseline; - Milk intake at 2y follow up (svg/d): <2 28.5%, 2 30.8%, >2 40.8%; Exclude: <2y of age, non-dairy milk drinkers, missing dietary or BMI data | Exposure: Milk intake (whole/2% & 1%/skim); participants who primarily drank soymilk or other milk alternatives were excluded from analyses; Other exposures:; Comparator: Continous intake; Assessment methods and timing: Interview with primary caregiver in the home regarding intake; represents usual weekly intake; Baseline, 2y follow-up; Outcomes and assessment methods:; - Height measured twice by trained researchers using stadiometer; - Weight measured twice by trained researchers using digital scale; - BMI calculated as weight in kilograms divided by height in meters squared; - Age- and gender-specific z-scores (BMIZ) calculated using CDC growth charts; - Weight categories: normal weight <85th%, overweight >85–95th%, obesity >95th%); - Baseline, 2y follow-up | [underlined: Overweight at age 4y], Logistic regression, OR (95% CI); 2%/whole at age 2y (ref); 1%/skim at age 2y: 1.63 (1.23, 1.86), P<0.0001; [underlined: Obesity at age 4y], Logistic regression; 2%/whole at age 2y (ref); 1%/skim at age 2y: 1.65 (1.31, 2.06), P<0.0001; [underlined: Change in BMIZ age 2y-4y], Linear regression; 2%/whole at age 2y & 4y (n=4900) 1%/skim at age 2y & 4y (n=250) P=0.6; [underlined: Change in raw BMI age 2y-4y], Linear regression; 2%/whole at age 2y & 4y (n=4900) 1%/skim at age 2y & 4y (n=250) NS, data not shown; [underlined: Developing Overweight/Obesity at age 4y], Logistic regression; 2%/whole at age 2y & 4y (ref, n=4900): 1%/skim at age 2y & 4y (n=250); 1.57 (1.03, 2.42), P=0.04 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, SEP, anthropometry at baseline, diet quality (juice and SSB); - Other: Maternal BMI; Limitations:; - Did not account for key confounders: Physical activity; - Potential risk of misclassification of exposures; Funding:; NIH
Striegel-Moore, 2006 ^30^; PCS, NHLBI Growth and Health Study, U.S.; Analytic N=2,371; Participant characteristics at baseline:; Female adolescents; - Age: 9–10y; - Female: 100%; - Race/ethnicity: Black 51%, White 49%; - SEP: SEP: <$10K: 17%; $10<20K: 14%; $20<30K: 15%; $30<40K: 14%; $40<50K: 12%; $50<75K: 17%; ≥$75K: 6%; - Anthropometry: Weight: ~ 37kg; Height: ~141 cm; - Physical activity: NR; - Smoking: NR; - Diet quality: Soda intake, g/d, Mean (SE): White, 135.45 (8.29); Black, 134.53 (7.85); - TEI: NR; Study beverage intake at baseline: Milk intake, g/d, Mean (SE): White, 352.04 (7.22); Black, 244.13 (5.36); Exclusion criteria: N/A | Exposure: Includes: all types of dairy milk: Whole, low-fat, skim milk, non-fat dry milk from powder, buttermilk, chocolate milk or cocoa, evaporated milk, milkshakes;; Excludes: chocolate-flavored drink, strawberry-flavored drink; Instant Breakfast, coconut milk, soy milk, yogurt drink.; Other exposures: 100% juice, SSB, LNCSB, Coffee/tea; Comparator: Continuous intake; Assessment methods and timing: Validated 3-d food records; represents usual intake over 3 consecutive days (2 weekdays and 1 weekend day); At baseline, and annually for years 1–5, then at years 7, 8, 10; Outcomes and assessment methods:; - Weight measured twice by research staff using electronic scale; - Height measured twice by research staff using stadiometer; - BMI calculated as weight in kilograms divided by height in meters squared Baseline, annually until 10y follow-up | [underlined: BMI], Linear regression; Change per 100g/d increase: B: −0.002, SE: 0.006, P>0.05 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, diet quality (other beverages); - Other: Study site; Limitations:; - Did not account for key confounders: SEP, anthropometry at baseline, physical activity; - No information on non-completers; No preregistered data analysis plan; Funding:; NHLBI
Tam, 2006 ^31^; PCS, Nepean Study, Australia; Analytic N=281; Participant characteristics at baseline: Children born term at Nepean Hospital, in western Sydney, between August 1989 and April 1990, part of a birth cohort designed to investigate the effects of birth size, body size and genes on blood pressure and bone mass.; - Age: Mean (SD) 7.7 (0.6)y; - Female: 50%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Normal BMI at 7y & 13y: 69%; BMI gainers: Normal BMI at 7y & Ovwt/Ob at 13y: 11%; BMI losers: Ovwt/Ob at 7y & Normal BMI at 13y: 5%; Ovwt/Ob at both 7y & 13y: 15%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: NR; Exclude: born preterm, incomplete data at baseline or follow up | Exposure: Milk (no further specification given); Other exposures: SSB (soft drink/cordial), SSB (fruit juice/drink); Comparator: Different intake level of milk; Assessment methods and timing: Estimated (household measurement) 3-day food record 7.7y; Outcomes and assessment methods:; Height and weight measured by study staff; CDC growth charts (2005) were used to determine overweight/obesity; Follow-up Mean (Range): 5.4 (4.0–6.6)y | [underlined: Weight status], Median ml of milk per day (5th-95th percentile), ANOVA; Acceptable BMI (n=195): 242 (0–645) ml; BMI gainers (n=32): 218 (0–657) ml; BMI losers (n=13): 193.5 (0–645) ml; Overweight/obesity at both time points (n=41): 243 (3–683) ml; P=0.995 | Model adjustments:; - TEI: No; - Key confounders: Sex, age, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: Race/ethnicity, SEP, physical activity, smoking, diet quality; - Exposure not well defined; Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; NR; broader cohort funding provided by the Children’s Hospital Clinical Research Grant Program and Pharmacia & Upjohn (Garnett, 2001)
Vanderhout, 2021 ^41^; PCS, TARGet Kids! (The Applied Research Group for Kids), Canada Analytic N=7,467; Participant characteristics at baseline:; Children; - Age: Mean (SD): 2.6 (1.5)y; - Female: 47%; - Race/ethnicity: Maternal ethnicity: 59% European; 6% East Asian; 8% South Asian; 3% Southwest Asian; 7% Arab or Affrican; 3% Latin American; 5% Mixed ethnicity; 0.3% Other; - SEP: Household income: 10% <$30k, 16% $30,000–79,999, 48% $80–150k, 3% >$150k; - Anthropometry: BMIz, Mean(SD) = 0.18(1.1); 2% Underweight, 77% Normal weight; 16% Overweight, 5% Obesity; - Physical activity: NR; - Smoking: NR; - Diet quality: Sugary drink intake (100% juice, fruit drinks, soft drinks), cups/d, mean (SD): 0.7 (1.1); - TEI: NR; Study beverage intake at baseline: Typical cow’s milk intake, Mean (SD)=1.9 (1.2) cups/d; 56% drank whole milk, 34% drank 2% milk, 8% drank 1% milk, and 3% drank skim milk; Included: Healthy children aged 9 months to 8y who reported consuming cow’s milk.; Excluded: Severe developmental delay, birth weight <2500g, chronic illness impacting metabolism (e.g., cystic fibrosis). | Exposure: Cow’s milk fat intake, including skim (0.1%), 1%, 2%, and whole (3.25%); cups/d; Other exposures:; Comparator: Continuous (by cow’s milk fat % intake); Categorical: whole milk (3.25%) vs. reduced fat milk (0.1–2%); Assessment methods and timing: Parent-completed dietary questionnaire (not validated) on child’s milk intake the past 3d (both type and amount in cups/d) At least one well-child visit (age 2, 4, 6, 9, 12, 18, and 24mo, and annually thereafter); mean follow-up duration was 2.7y (SD 1.7); 63% (n=4699) had repeated measures.; Outcomes and assessment methods:; Height and weight (length for children <2y) were measured by trained research assistants and used to calculate BMI. zBMI (and weight status categories) were determined according to WHO growth standards. WHO weight classifications for children over age 5y were applied to all children.; At each well-child visit (age 2, 4, 6, 9, 12, 18, and 24mo, and annually thereafter); mean follow-up duration was 2.7y (SD 1.7) | [underlined: BMI z-score], β (95% CI) with every 1% increase in cow’s milk fat intake; −0.05 (−0.07, −0.03), p<0.0001; Sensitivity analysis for children over age 2–8y:; −0.07 (−0.09, −0.05), p<0.0001; [underlined: Overweight (1 < BMIz ≤ 2)], OR (95% CI); Whole vs 0.1–2%: 0.84 (0.77, 0.91), p<0.0001; Whole vs 2%: 0.81 (0.74, 0.89), p<0.0001; Whole vs 1%: 0.96 (0.82, 1.11), p=0.57; Whole vs 0.1%: 0.83 (0.66, 1.03), p=0.09; Sensitivity analysis for children over age 2–8y:; Whole vs 0.1–2%: 0.90 (0.80, 1.00), p=0.05; [underlined: Obesity (BMIz > 2)], OR (95% CI); Whole vs 0.1–2%: 0.82 (0.68, 1.00), p=0.047; Whole vs 2%: 0.83 (0.68, 1.00), p=0.05; Whole vs 1%: 0.87 (0.66, 1.16), p=0.35; Whole vs 0.1%: 0.69 (0.45, 1.05), p=0.08 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, SEP, diet quality (volume of sugary drink intake consumed in 250 ml cups/d); - Other: volume of cow’s milk consumed per day; birthweight; breastfeeding duration; parent BMI; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity; - Start of follow-up and exposure do not coincide; Exposure assessment tool not validated; Exposure data only measured at baseline; No preregistered data analysis plan; Funding:; Canadian Institutes of Health Research Institute of Human Development, Child and Youth Health
Vanselow, 2009 ^37^; PCS, Project EAT, U.S.; Analytic N=2,294; Participant characteristics at baseline:; Adolescents; - Age: 14.9y (11–18y); - Female: 55%; - Race/ethnicity: 62.9% white, 17.9% Asian American, 9.7% African American, 3.9% Hispanic, 2.7% American Indian, 2.9% mixed/other; - SEP: Parent education level (highest), %, chi-square test: *unclear what "highest" means; White milk:; 0 servings/wk: 7.9%; 0.5–6 servings/wk: 12.4%; ≥7 servings/wk: 21.3%; P<0.05; Chocolate milk:; 0 servings/wk: 18.9%; 0.5–6 servings/wk: 17.2%; ≥7 servings/wk: 10.4% P<0.05; - Anthropometry: NR; - Physical activity: Strenuous exercise, hr/wk, mean (SE), chi-square test White milk:; 0 servings/wk: 3.5 (0.1); 0.5–6 servings/wk: 3.6 (0.1); ≥7 servings/wk: 4.1 (0.0); P<0.05; Chocolate milk:; 0 servings/wk: 3.8 (0.0); 0.5–6 servings/wk: 4.0 (0.0); ≥7 servings/wk: 4.1 (0.1); P<0.05; - Smoking: NR; - Diet quality: NR; - TEI: Kcal/d, mean (SE), chi-square test White milk:; 0 servings/wk: 1577 (77); 0.5–6 servings/wk: 1839 (35); ≥7 servings/wk: 2256 (26); P<0.05; Chocolate milk:; 0 servings/wk: 1836 (29); 0.5–6 servings/wk: 2187 (30); ≥7 servings/wk: 2802 (71); P<0.05; Study beverage intake at baseline: White milk (n=2159, 6% missing data): 7.4% 0 servings/wk, 32.9% 0.5–6 servings/wk, 59.7% ≥7 servings/wk; Chocolate milk (n=2156, 6% missing data): 47% 0 servings/wk, 45.2% 0.5–6 servings/wk, 7.8% ≥7 servings/wk; Included: participants of Project EAT-1 cohort (adolescents living in a metropolitan area and attending public middle or high schools); Excluded: lost to follow-up, those who did not complete FFQ at time 1 or time 2, had implausible energy intakes, and did not report BMI at time 1 or time 2. | Exposure: Milk: milk and chocolate milk. No information on fat content. Serving size NR.; Other exposures: SSBs, LNCSB, 100% juice; Comparator: Different intake of milk, categorical intake (0, 0.5–6, ≥7 servings/wk); Assessment methods and timing: Validated 149-item youth and adolescent food-frequency questionnaire (YAQ).; Responses ranged from “never/less than once per month” to ≥4 glasses, cups, cans, or drinks per day depending on beverage type.; Baseline, 5y follow up; Outcomes and assessment methods:; BMI calculated from self-reported height and weight. Overweight considered as BMI ≥85th percentile for sex and age; Measured at: Baseline, 5y follow up | [underlined: Change in BMI over 5y] by number of servings/wk of time 2 milk intake, kg/m2, mean (SE), multivariable linear regression; [underlined: White milk]; 0 servings/wk: 2.34 (0.24); 0.5–6 servings/wk: 1.68 (0.11); ≥7 servings/wk: 1.93 (0.11); P=0.03; [underlined: Chocolate milk]; 0 servings/wk: 1.89 (0.10); 0.5–6 servings/wk: 1.77 (0.12); ≥7 servings/wk: 2.43 (0.44); P=0.31 | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, SEP, anthropometry at baseline, physical activity (models 2 and 3); - Other: Model 1: key confounders as listed; baseline beverage consumption of the beverage being analyzed; Model 2: all beverages assessed together in the model; adjusted for key confounders and all baseline beverages, cohort, change in BMI, baseline and time 2 strenuous physical activity, and time 2 weekday television watching and coffee and tea consumption; Model 3: soft drinks, low-calorie soft drinks and white milk assessed together in the model; adjusted for key confounders; baseline white milk, soft drink, and low-calorie drink consumption, baseline and time 2 strenuous physical activity, time 2 weekday television watching and coffee and tea consumption, and dieting and parental weight-related concerns; Limitations:; - Did not account for key confounders: diet quality; - No information on non-completers; Lack of accurate assessment of exposure portion sizes; No preregistered data analysis plan; Funding:; HHS (Maternal and Child Health Bureau, Health Resources and Services Administration)
Whetstone, 2012 ^40^; PCS, North Carolina Health and Wellness Trust Fund programs (NRCT), U.S.; Analytic N=1,144; Participant characteristics at baseline:; Children; - Age: Mean (SD): 9.5 (4.1) y, Range: 4.1–18.6y; - Female: 52%; - Race/ethnicity: African-American 35.3%, Hispanic/Latino origin 2.6%, White 64.7%,; - SEP: NR; - Anthropometry: BMI z-score: 0.82 (1.13); Weight status: underweight=1.6%, healthy weight=55.0%, overweight=16.9%, obesity=26.6%; - Physical activity: Mean number of days of exercise or physical activity per week: 4.49; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: Whole milk intake at baseline: 43.6%; Exclude: missing height, weight, sex or race data | Exposure: Change in milk intake (from whole milk to low-fat milk); Other exposures: SSB; Comparator: No change in milk intake; Assessment methods and timing: Unvalidated health survey completed by parents (if child was grade K-5) or self (if child was grade 6–12); At baseline and every 6 months during follow-up period; average follow-up 20.5mo (range: 8–29mo); Outcomes and assessment methods:; - Height measured by trained staff, stadiometers recommended but alternative instructions for triangular ruler and metal tape measure provided; - Weight measured by trained staff using balance beam or digital scale; - BMI z-score (BMIZ) calculated using approach on CDC website; - Weight status were age- and gender-specific CDC designations: underweight (BMI<5%), healthy weight (5%≤BMI<85%), overweight (85%≤BMI<95%), obesity (BMI≥95%); At baseline and every 6 months during follow-up period; average follow-up 20.5y (range: 8–29mo) | [underlined: Weight Status], Percentage of children with overweight/obesity who lowered their weight status category (subgroup n NR), Chi-square difference; Did not change to lower fat milk vs Changed to lower fat milk: 17.9% vs 39.6%, P=0.003; [underlined: BMIZ], Change in BMIZ among children with overweight/obesity (subgroup n NR), ANOVA; Did not change to lower fat milk vs Changed to lower fat milk: −0.08 vs −0.22, p>0.05 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race and/or ethnicity, anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: SEP, physical activity, diet quality; - Exposure not clearly defined; tool not validated; Subgroup analyses reported; Results from full sample NR; no preregistered data analysis plan; Funding:; North Carolina Health and Wellness Trust Fund Commission
Wrotniak, 2019 ^43^; PCS, Secondary analysis of ’Mind Your Body’ RCT, U.S.; Analytic N=91; Participant characteristics at baseline:; Adolescents undergoing obesity treatment; - Age: 10–14y; - Female: 65%; - Race/ethnicity: White: 33%; Black: 63%; Other: 4%; - SEP: NR; - Anthropometry: Mean BMI 33 kg/m2; Mean BMIz 2.39 SD; - Physical activity: NR; - Smoking: 100% no cigarette smoking (exclusion criteria); - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: Baseline (n=87); Unflavored milk, Mean (95% CI) = 0.57 (0.45, 0.69) svg/d; Flavored milk, Mean (95% CI) = 0.15 (0.08, 0.21) svg/d; Included participants ≥10y and <15 with a BMI ≥ 97th% for age and sex.; Excluded participants if BMIz >3.0 SD to avoid severe co-morbidities; those with syndromic or secondary obesity, psychosis, eating disorders, orthopedic problems interfering with physical activity, weight loss medications, cigarette smoking, and any other medications or chronic conditions that could interfere with intervention | Exposure: Dairy milk (unflavored and flavored); 8 oz serving per day; Other exposures:; Comparator: Continuous intake of milk consumption; Assessment methods and timing: 3d dietary recall (2 week days, 1 weekend) by bionutritionists via telephone interview; At baseline, 6mo, and 12mo; Outcomes and assessment methods:; Weight measured on digital electronic scale and height on stadiometer by trained research staff in triplicate. BMI calculated from height and weight and converted to z-score using CDC growth charts; At baseline, 6mo, and 12mo | [underlined: ΔBMI z-score] (SD), β (95% CI), linear mixed effects regression; Unflavored milk: 0.0044 (−0.0046, 0.0134); Flavored milk: 0.0095 (−0.0133, 0.0323) P-value: NS; [underlined: ΔBMI] (kg/m2), β (95% CI), linear mixed effects regression; Unflavored milk: 0.021 (−0.072, 0.113); Flavored milk: 0.022 (−0.232, 0.276) P-value: NS; [underlined: ΔWeight] (kg), β (95% CI), linear mixed effects regression; Unflavored milk: 0.213 (−0.008, 0.434); Flavored milk: −0.021 (−0.626, 0.584) P-value: NS | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, SEP (family income, and maternal and paternal education), anthropometry at baseline, physical activity, diet quality (energy-adjusted intake of fruits, vegetables, whole-grain breads, SSBs); - Other: study and intervention condition, sedentary behavior; Limitations:; - No preregistered data analysis plan; May not be generalizable since participants were part of a weight loss intervention; Funding:; NIH; Dairy Research Institute
Zheng, 2015^32^; PCS, Childhood Asthma Prevention Study (RCT), Australia; Analytic N=158; Participant characteristics at baseline:; Children; - Age: Mean: ~8y; - Female: 48%; - Race/ethnicity: Mother born in Australia/New Zealand ~78%; Father born in Australia/New Zealand ~73%; - SEP: Maternal education level >12y; ~55%; Paternal education level >12y; ~58%; Living in disadvantaged area ~20%; - Anthropometry: BMI z-score, Mean (SD): 0.4(1.0); Overweight/obesity: 27.2%; - Physical activity: NR; - Smoking: NR; - Diet quality: Macronutrient intake data in paper; - TEI: Mean ~8.0 MJ/d (~1,912 kcal/d); Study beverage intake at baseline: Milk intake at baseline (g/d), Mean (SD): ~280(151); Exclude: incomplete diet data, misreporting of energy intake, missing anthropometric data | Exposure: Milk intake (full fat, reduced fat, skim, and flavored); Other exposures: 100% juice, SSB, LNSBC; Comparator: Continuous intake; Assessment methods and timing: Three 24-hr dietary recalls via phone using multiple pass approach completed by children with parental assistance; Represents usual dietary intake on nonconsecutive weekdays and weekends At 1y follow-up (age 9y); Outcomes and assessment methods:; - Weight measured to nearest 0.1kg; - Height measured using stadiometer; - Age- and sex-specific BMI z-scores (BMIZ) calculated using 2000 CDC growth charts; - Percentage body fat (%BF) measured by bioimpedance analysis; Baseline (age 8y), and 3.5y follow-up (age 11.5y) | [underlined: %BF], Linear regression; Change per 100 g/d increase, β (SE):; TEI unadj: 0.12 (0.29), P=0.68; TEI adj: 0.37 (0.31), P=0.24; [underlined: BMIZ], Linear regression; Change per 100 g/d increase, β (SE):; TEI unadj: 0.01 (0.03), P=0.79; TEI adj: 0.05 (0.03), P=0.16 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP, anthropometry at baseline; - Other: Maternal age at birth, presence of gestational diabetes, exclusive breastfeeding at 3mo, pubertal status, randomization group (omega-3 fatty acid dietary supplementation and house dust mite reduction); Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity, diet quality; - Exposure measured at baseline only; Baseline data for exposure and outcome occrred 1 year apart; Funding:; National Health and Medical Research Council of Australia; Cooperative Research Centre for Asthma; New South Wales Department of Health; Children’s Hospital Westmead
Zheng, 2015 ^33^; PCS, Healthy Start Study (RCT), Denmark; Analytic N=352; Participant characteristics at baseline:; Children; - Age: Mean (SD): 4.1y (1.1); - Female: 45%; - Race/ethnicity: NR; - SEP: Maternal education level, Tertiary or above: 78.0%; Paternal education level, Tertiary or above: 61.0%; Parents divorced 5.6%; - Anthropometry: Mean (SD), Body weight (kg): 18.0 (3.3); BMI z-score: 0.3 (0.9); - Physical activity: High: 59.2%; - Smoking: NR; - Diet quality: SSB, g/d, Mean (SD): 92 (107); - TEI: Mean (SD): 4.97mJ/d (0.95) (~1,195 kcal/d); Study beverage intake at baseline: Milk intake at baseline (g/d), Mean (SD): 259.6 (167.5); Exclude: missreported energy intake, incomplete diet data | Exposure: Milk intake (skimmed, low-fat, whole, buttermilk, flavored); Other exposures: SSB, LNCSB; Comparator: Continuous intake; Assessment methods and timing: 4-d dietary record completed by parents; represents dietary intake on both weekdays and weekends; Baseline, 1.5y follow up; Outcomes and assessment methods:; - Height measured using stature meter; - Weight measured using mechanical weight or beam-scale; - Age- and sex-specific BMI z-scores (BMIZ) calculated using Lambda-Mu-Sigma method; Baseline, 1.5y follow up | Nutrient Residual Model (includes beverage intake residuals and total energy intake); [underlined: BMIZ], Linear regression; Change per 100 g/d increase: B: −0.02, SE: 0.02, P=0.41; [underlined: Body weight], Linear regression; Change per 100 g/d increase: B: −0.07, SE: 0.05, P=0.13; Energy Partition Model (includes absolute amount of individual beverage intake and energy from non-beverage sources); [underlined: BMIZ], Linear regression; Change per 100 g/d increase: B: −0.01, SE: 0.02, P=0.66; [underlined: Body weight], Linear regression; Change per 100 g/d increase: B: −0.07, SE: 0.04, P=0.20 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, SEP, anthropometry at baseline, physical activity, diet quality (other beverages); - Other: Intervention allocation, parents divorced, number of siblings living with the child, maternal pre-pregnancy overweight; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - No information on non-completers; No preregistered data analysis plan; Funding:; No funding received
Zheng, 2015 ^34^; PCS, European Youth Heart Study (EYHS), Denmark; Analytic N=358; Participant characteristics at baseline:; Children; - Age: Mean (SD): 9.6y (0.4); - Female: 56%; - Race/ethnicity: NR; - SEP: 47% Low (elementary, high school, or vocational education); - Anthropometry: BMI 17.2 (2.3) kg/m2; BMI z-score 0.4 (1.1); - Physical activity: 55% Active (regular exercise); - Smoking: NR; - Diet quality: SSB, g/d, Mean (SD): 154 (205); - TEI: yes and no; Study beverage intake at baseline: Milk intake: 481.2 (290.9); Exclude: incomplete diet or anthropometric data; underreporting energy intake | Exposure: Milk intake (regular, low-fat, skim, plain, or flavored); Other exposures: 100% juice, SSB, Coffee/tea; Comparator: Continuous intake; Assessment methods and timing:; One 24h recall face-to-face interview supplemented with parent-assisted food record; represents food intake; Baseline; Outcomes and assessment methods:; - Height measured bare feet to nearest 5mm using stadiometer; - Weight measured to nearest 0.1 kg using beam balance scale; - BMI calculated as kg/m2; - Age- and sex-specific BMI z-score (BMIZ) generated using the least mean squares method; - Waist circumference (WC) measured twice with metal anthropometric tape (mean was used); - Sum of 4 skinfolds (Σ4SF) obtained by adding average skinfolds of 4 sites (biceps, triceps, subscapular, and suprailiac) that were measured in duplicate with Harpenden fat calipers Baseline, 6y follow up | Base Model (Model 1 in paper) adjusted for confounders listed to the right, but did not adjust for TEI; Standard Multivariate Model (Model 2 in paper) adjusted for TEI; Energy Partition Model (Model 3 in paper) included energy-containing beverages only (ie, excluded water) and adjusted for energy from non-beverage sources.; [underlined: Change in WC age 9–15y]: Per 100 g/d increase, Linear regression, β (SE), n=314; Base Model: −0.13 (0.11), P=0.22; TEI Model: −0.05 (0.12), P=0.65; Energy Partition: −0.09 (0.11), P=0.41; [underlined: Change in Σ4SF age 9–15y]: mm, Per 100 g/d increase, Linear regression, β (SE), n=308; Base Model: 0.04 (0.26), P=0.87; TEI Model: 0.12 (0.29), P=0.67; Energy Partition: 0.09 (0.26), P=0.74; [underlined: Change in BMI age 9–15y]: kg/m2, Per 100 g/d increase, Linear regression, β (SE), n=314; Base Model: −0.003 (0.01), P=0.79; TEI Model: −0.001 (0.01), P=0.95; Energy Partition: −0.003 (0.01), P=0.81 | Model adjustments:; - TEI: yes and no; - Key confounders: Sex, age, SEP, anthropometry at baseline, physical activity, diet quality (other beverages); - Other: Pubertal status, Sex x SEP, individual beverage intakes, energy from non-beverage sources; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Exposure measured at baseline only; No preregistered data analysis plan; Funding:; NR

a BMI: body mass index; CI: confidence interval; CDC: Centers for Disease Control; d: day(s); EPIC: European Prospective Investigations into Cancer and Nutrition Study; FFQ: food frequency questionnaire; g: gram(s); HAZ: height-for-age z-score; hr: hour; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); L: liter; LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NHS: Nurses’ Health Study; NIH: National Institutes of Health; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; REF: reference group; RCT: Randomized controlled trial; SD: standard deviation; SE: standard error; SEP: Socioeconomic position; SSB: sugar-sweetened beverage(s); svg: serving(s); TEI: total energy intake; USDA: United States Department of Agriculture; WHZ: weight-for-height z-score; wk: week(s); y: year(s)

Table 16 Risk of bias for non-randomized controlled trials examining dairy milk and milk alternative consumption in children and adolescents and growth, body composition, and risk of obesity^a^

Article | Randomization | Identification of participants-randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Arnberg, 2012 ^1^ | LOW | Not applicable | LOW | LOW | LOW | LOW | LOW
Lambourne, 2013 ^2^ | SOME CONCERNS | Not applicable | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Larnkjaer, 2014 ^3^ | LOW | Not applicable | LOW | LOW | LOW | LOW | LOW
Larnkjaer, 2015 ^4^ | LOW | Not applicable | LOW | LOW | LOW | LOW | LOW
Rahmani, 2011 ^5^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 17 Risk of bias for non-randomized controlled trials examining dairy milk and milk alternative consumption in children and adolescents and growth, body composition, and risk of obesity^a^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Gomez, 2021 ^6^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE | SERIOUS
Ho, 2005 ^38^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE | SERIOUS

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 18 Risk of bias for observational studies examining dairy milk and milk alternative consumption in children and adolescents and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Berkey, 2004 ^8^ | HIGH | LOW | LOW | LOW | HIGH | LOW | HIGH | VERY HIGH
Berkey, 2005 ^9^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | LOW | HIGH
Berkey, 2009 ^7^ | HIGH | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Blum, 2005 ^10^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Choi, 2022 ^11^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS
DeBoer, 2015 ^12^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dong, 2015 ^36^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Dubois, 2016 ^13^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Faith, 2006 ^14^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Fiorito, 2009 ^15^ | HIGH | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
Haines, 2007 ^16^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH
Hasnain, 2014 ^17^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Huh, 2010 ^18^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Johnson, 2007 ^19^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kral, 2008 ^20^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kunaratnam, 2020 ^21^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | VERY HIGH | LOW | SOME CONCERNS | VERY HIGH
Laurson, 2008 ^22^ | HIGH | HIGH | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Lin, 2012 ^23^ | LOW | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Marabujo, 2018 ^24^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Marshall, 2018 ^25^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Marshall, 2019 ^26^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
McGovern, 2022 ^35^ | LOW | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Newby, 2004 ^27^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Noel, 2011 ^28^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Noel, 2013 42 | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Sakaki, 2021 ^29^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Scharf, 2013 ^39^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Striegel-Moore, 2006 ^30^ | HIGH | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Tam, 2006 ^31^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | LOW | HIGH
Vanderhout, 2021 ^41^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | HIGH
Vanselow, 2009 ^37^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Whetstone, 2012 ^40^ | HIGH | SOME CONCERNS | VERY HIGH | LOW | HIGH | LOW | HIGH | VERY HIGH
Wrotniak, 2019 ^43^ | LOW | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Zheng, 2015 ^32^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Zheng, 2015 ^33^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Zheng, 2015 ^34^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 19 Evidence examining the relationship between dairy milk and milk alternative consumption in adults and older adults and body composition and risk of obesity^a^

Study and Population Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Confounding and Study Limitations
Randomized controlled trials
Barr, 2000^44^; RCT-Parallel, US; Baseline N=204, Analytic N=200 (Attrition: 2%); Power: Power: n=105/group, to detect 1.3 kg difference with 5% dropout, B=0.80, α=0.05; Participant characteristics at baseline:; Older adults; - Age: Mean (SD): 65y (6.7); Range: 55–85y; - Female: 65%; - Race/ethnicity: White: 95%; - SEP: Education, Mean (SD): 15.1y (3.3); - Anthropometry: BMI, Mean (SD): 25.9 (3.5); - Physical activity: NR; - Smoking: NR; - Diet quality: Vitamin and mineral intakes presented in paper; - TEI: Kcal/d, Mean (SD):; Women: 1,678 (353); Men: ,2203 (503); - Study beverage intake at baseline: All ≤1.5 serv/d of dairy at baseline; Include: good general health, age 55–85y, consume <1.5 dairy serv/d, BMI 16–36, ≥5y postmenopause, no calcium supplementation for >4wk before enrollment, stable hypertension or hyperlipidemia medication dosage for ≥4wk before enrollment, stable HRT for ≥1y before enrollment; Exclude: diabetes, chronic or life-threatening diseases, serious health abnormality, BP >170mmHg systolic or 95mmHg diastolic, total cholesterol >6.75mmol/L, fasting glucose >7.8mmol/L | Intervention: Addition of 3, 8-oz servings of skim or 1% fluid dairy milk to their usual diet (n = 98); Study purpose: To assess the impact of increased consumption of milk, without other dietary advice, on older adults’ energy and nutrient intakes, weight, cardiovascular risk factors (blood pressure, plasma lipid levels), and quality of life; Comparator: Control (usual intake), n = 102; Duration: 12wk; Compliance: Glasses/d at:; wk 4, women 2.9, men 3.1;; wk 8, women 2.9, men 3.2;; wk 12, women 2.9, men 3.0; Outcomes and assessment methods:; - Measured by study personnel; - Baseline, 4wk, 8wk, 12wk | Per-protocol analyses; [underlined: Weight], kg, Mean (SD), kg, Linear regression; Over time: baseline, 4wk, 8wk, 12wk; [underlined: Women]:; Control (n=66): 66.7 (11.4), 67.1 (11.5), 66.9 (11.5), 67.1 (11.4); Milk (n=63): 67.6 (10.0), 68.2 (10.0), 68.2 (10.1), 68.5 (10.1); [underlined: Men]:; Control (n=36): 81.1 (9.1), 81.8 (9.1), 82.2 (9.2), 82.1 (9.5); Milk (n=35): 84.5 (11.8), 85.9 (11.7), 85.6 (11.8), 86.1 (11.8); Weight increased over time in both intervention and control groups (p<0.001); Group*Time Interaction: Milk group gained 0.6 kg more than control group, p<0.005 | Model adjustments:; - TEI: no; - Other:; Limitations:; - Randomization method NR No preregistered analysis plan; Funding:; International Dairy Foods Association
Chee, 2003^45^; RCT-Parallel, Malaysia; Baseline N=200, Analytic N=173 (Attrition: 14%); Power: NR; Participant characteristics at baseline:; Adults, healthy postmenopausal women; - Age: Mean (SD), 59 (3) y (Range: 55–65y); - Female: 100%; - Race/ethnicity: 100% Chinese; - SEP: NR; - Anthropometry: BMI Mean (SD), 23.8 (3.6) kg/m2; - Physical activity: Physical activity score, Mean: 105 (units NR); - Smoking: NR; - Diet quality:; - TEI: Mean: ~6,485 kJ/d (~1,550 kcal/d); Study beverage intake at baseline: Milk intake <2 glasses/d (inclusion criteria); Included: Chinese women aged 50–65y and >5y postmenopausal; Excluded: history of bone disease or medical conditions that affect bone metabolism or had other chronic illnesses; those taking calcium supplements (>500 mg/d for longer than a month or were already drinking 2 or more glasses of milk a day | Intervention: High-calcium skimmed milk (50g powder reconstituted with 400mL water/d); asked to maintain usual physical activity and dietary patterns; given advice to adjust energy intake to compensate for additional calories provided by milk (n=91); Study purpose: to study the effect of a milk supplement on bone mineral density in healthy postmenopausal Chinese women in Malaysia; Other interventions: NA; Comparator: Control: maintain usual diet and physical activity (n=82); Duration: 2 years; Compliance: Participants recorded number of milk sachets consumed/d; random home visits and phone calls; Mean=92%, SD=7.9%, Range: 64–100%; Outcomes and assessment methods:; - Height and weight measured by study personnel; Lean body mass and body fat percentage measured by DXA; - Baseline, 6mo, 12mo, 18mo, 24mo | Per-protocol analyses; [underlined: Body fat (kg)]; Baseline, Mean absolute change (SE); Control: 36.1 (6.8)%, −0.04 (0.02); Milk: 35.2 (6.1)%, −0.04 (0.12); Change over 24mo, between groups: P=NS; [underlined: Lean body mass (kg)]; Baseline, Mean absolute change (SE); Control: 33.0 (3.7), −0.03 (0.01); Milk: 32.7 (4.1), −0.02 (0.01); Change over 24mo, between groups: P=NS; [underlined: Weight (kg)]; Baseline, Mean absolute change (SE); Control: 57.2 (9.4), 0.16 (0.29); Milk: 56.1 (8.9), 0.04 (0.27); Change over 24mo, between groups: P=NS | Model adjustments:; - TEI: yes; - Other:; Limitations:; - No power calculation; No preregistered data analysis plan; Funding:; New Zealand Milk
Chiang, 2021^46^; RCT - Parallel, Taiwan; Baseline N=36, Analytic N=35 (Attrition: 3%); Power: NR; Participant characteristics at baseline: Elderly nursing home residents with sarcopenia (>75% categorized as severe sarcopenia at baseline); - Age: Mean~85y (range 78–93y); - Female: 17%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean baseline weight: ~57 kg; Mean baseline BMI: ~22.3 kg/m2; Mean baseline % body fat: ~32%; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Mean TEI: ~1793 kcal/day; Study beverage intake at baseline: NR; Included: Taiwanese adults >75y with sarcopenia in a nursing home; Excluded: milk or soy milk allergy; inability to participate in resistance training exercise; dx of cancer, chronic liver disease, and/or kidney dialysis | Intervention: 200 mL milk twice daily (400 mL/day) + mild resistance exercise, n=12; OR; 200 mL soy milk twice daily (400 mL/day) + mild resistance exercise, n=11; Study purpose: to investigate the beneficial effects of milk or soy milk combined with resistance exercise on the muscle mass and muscle strength of individual elderly nursing home residents with sarcopenia; Other interventions: None; Comparator: Mild resistance exercise + 200mL water (n=12); Duration: 12wk; Compliance: NR; Outcomes and assessment methods:; - BMI: calculated based on body weight and height (likely measured, not self-report, but study is unclear); Fat mass and lean mass: DXA scan Muscle mass and body fat: bioelectrical impedance analysis (BIA); - Baseline, 6wk, 12wk | [underlined: Body fat %], mean (SD); [underlined: Within group]: Baseline, 6wk, 12wk; Milk: 32.7 (5.6), 29.3 (7.7), 30.9 (6.0); Soymilk: 32.3 (6.5), 32.4 (8.1), 32.8 (7.7); Comp: 30.6 (8.6), 29.9 (9.1), 31.7 (8.8); [underlined: Between groups]: NS; Appendicular skeletal muscle mass Index, (kg/m2)^3, mean (SD); [underlined: Within group]: Baseline, 6wk, 12wk; Milk: 6.2 (0.5), 6.2 (0.6), 6.0 (0.6); Soymilk: 6.0 (0.7), 6.1 (0.7), 6.1 (0.7); Comp: 6.1 (0.6), 6.0 (0.6), 6.0 (0.7); [underlined: Between groups]: NS; [underlined: BMI], kg/m^2^, mean (SD); [underlined: Within group]: Baseline, 6wk, 12wk; Milk: 22.1 (3.2), 22.4 (3.0), 22.6 (3.1); Soymilk: 22.6 (2.2), 22.6 (2.7), 23.1 (2.5); Comp: 22.1 (2.4), 21.5 (4.1), 22.3 (2.3); [underlined: Between groups]: NS; [underlined: Body weight], kg, mean (SD); [underlined: Within group]: Baseline, 6wk, 12wk; Milk: 58.3 (9.1), 59.2 (9.1), 59.7 (9.0); Soymilk: 55.4 (8.7), 55.2 (9.2), 56.4 (9.1); Comp: 56.2 (8.6), 54.7 (11.9), 56.7 (8.4); [underlined: Between groups]: NS | Model adjustments:; - TEI: No; - Other:; Limitations:; - Methods for randomization and concealment NR; No power calculation - likely underpowered ("sample size was too small"); No information on non-completers; No preregistered data analysis plan; Lack of generalizability; Interpretation complicated by multiple comorbidities of participants; Unable to isolate the effect of the beverage alone (all interventions included a physical activity component); Funding:; Taipei Veterans General Hospital Yuanshan Branch, Formosa Produce Corporation, Taipei, Taiwan
Daly, 2006 ^47^; RCT - Parallel, Australia; Baseline N=167, Analytic N=149 (Attrition: 11%); Power: NR; Participant characteristics at baseline:; Middle-aged to older men; - Age: Mean (SD): 62 (8)y; - Female: 0%; - Race/ethnicity: White: 100%; - SEP: NR; - Anthropometry: BMI Mean: 26.4kg/m2; - Physical activity: Energy expenditure in moderate activities, Mean~8751 kJ/wk (~2092 kcal/wk); Weight-bearing activities, Mean~5.5 hr/wk; - Smoking: Current smoker: 5%; - Diet quality: NR; - TEI: Mean: ~8,808 kJ/d (~2,105 kcal/d); Study beverage intake at baseline: NR; Include: Age >50y; Exclude: Calcium and/or Vitamin D supplementatoin in past 12mo; regular, high-intensity resistance training in past 6mo or >150min/wk of moderate- to high-impact weight-bearing exercise; BMI >35kg/m2; lactose intolerant; >4 alcoholic beverages/d; history of osteoporotic fracture; or medical disease or medication use known to affect bone metabolism | Intervention: 1% milk fortified with calcium and vitamin D, 400mL/d in addition to usual milk intake; Study purpose: to assess the effects of calcium and vitamin D3 fortified milk on BMD in community living men >50 years of age; Other interventions:; Comparator: Usual diet; Duration: 2 years; Compliance: Percentage of milk tetra packs consumed based on daily diaries: 85.1%; Outcomes and assessment methods:; - Weight measured with electronic scale; - Height measured using stadiometer; - BMI calculated as kg/m2; - Baseline, 6mo, 12mo, 18mo, 24mo | [underlined: Weight], kg, Linear regression, Mean (95% CI); [underlined: 6mo change]; Within group:; Control: −0.40, P=NS; Milk: 0.14, P=NS; Between groups: 0.54 (−0.27, 1.36), P=NS; [underlined: 12mo change]; Within group:; Control: 0.01, P=NS; Milk: 0.75, P<0.05; Between groups: 0.74 (−0.17, 1.64), P=NS; [underlined: 18mo change]; Within group:; Control: −1.08 (0.2, 1.9), P<0.001; Milk: 0.18, P=NS; Between groups: 1.26 (0.22, 2.29), P<0.01; [underlined: 24mo change]; Within group:; Control: −0.11, P=NS; Milk: 0.68, P=NS; Between groups: 0.79 (−0.40, 1.97), P=NS | Model adjustments:; - TEI: No; - Other:; Limitations:; - Method of allocation concealment NR; no power calculation; no preregistered data analysis plan; racial/ethnic minorities under-represented in study sample; Funding:; Geoffrey Gardiner Dairy Foundation; Helen M Schutt; Faculty of Health and Behavioural Sciences, Deakin University
Maersk, 2012 ^48^; RCT-Parallel, Denmark; Baseline N=60, Analytic N=47 (Attrition: 22%); Power: NR; Participant characteristics at baseline:; Adults with overweight and obesity; - Age: ~39y (Range 20–50y); - Female: 72%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI ~32 kg/m2 (Range 26–40); - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: NR; Included: healthy, nondiabetic participants with a BMI between 26–40 kg/m2, age 20–50y, and blood pressure <160/100 mm Hg. | Intervention: Semiskim milk (Arla Foods; 1 L/d), n=12; Study purpose: to compare the effects of sucrose-sweetened soft drinks with those of isocaloric milk and a noncaloric soft drink on changes in total fat mass and ectopic fat deposition (in liver and muscle tissue); Other interventions: sucrose-sweetened soft drink, aspartame-sweetened diet cola; Comparator: Still mineral water (Aqua d’or; 1 L/d), n=13; Duration: 6mo; Compliance: Empty bottles or cartons every 3–4wk; 7-d dietary records at baseline, 3mo, 6mo; compliance NR; Outcomes and assessment methods:; - Weight: method NR; Total fat mass and lean body mass determined by DXA; - At baseline, 6mo follow-up | ITT analyses; [underlined: Total fat mass, kg] at 6mo, ANOVA, Mean (SEM); Percent change over time, between groups:; Water: 0.490 (2.6); Milk: 1.42 (2.5); p > 0.05; [underlined: Lean mass, kg] at 6mo, ANOVA, Mean (SEM); Percent change over time, between groups:; Water: −0.189 (0.8); Milk: 1.43 (0.8); p > 0.05; Data are also provided on subcutaneous abdominal adipose tissue (SAAT), visceral adipose tissue (VAT), and the ratio of the two; none were significant for the exposures of interest.; [underlined: Weight], kg at 6mo, ANOVA, Mean (SEM) Percent change over time, bet ween groups:; Water: 0.576 (1.0); Milk: 1.36 (1.1); p > 0.05 | Model adjustments:; - TEI: No (but between-group differences NS at baseline or during study); - Other: N/A; Limitations:; - Baseline differences in VAT, skeletal muscle fat, and liver fat between groups; Methods for randomization and concealment NR; No power calculation; No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; The Food Study Group/Danish Ministry of Food, Agriculture and Fisheries; Novo Nordic Foundation; Clinical Institute at Aarhus University, Denmark; Danish Dairy Company, Arla Foods
Rosado, 2011 ^49^; RCT-Parallel, Mexico; Baseline N=139, Analytic N=127 (Attrition: 9%); Power: Sample size determined to detect a minimal expected weight change of 2.4 kg after 16wks; Type 1 error = 5%; Type 2 error = 20%; estimated lost-to-follow-up rate = 35%. Estimated 46 women/group needed to be adequately powered.; Participant characteristics at baseline:; Adult women with obesity; - Age: Mean (SD): 34 (6)y; - Female: 100%; - Race/ethnicity: All Mexican; - SEP: NR; - Anthropometry: Weight: ~79.6 kg BMI: ~35 kg/m2; WC: ~106 cm; - Physical activity: NR, participants asked to maintain habitual during study; - Smoking: NR; - Diet quality: Energy-restricted diet included meal plans designed by study staff with specific quantities of foods to be consumed for each of 3 daily meals; fruits and vegetables allowed as snacks between meals; - TEI: ~1933 kcal/d; Study beverage intake at baseline: <3 servings/day of milk or dairy products at baseline (inclusion criterion); Included: Women with BMI ≥30, aged between 25–45y, from 5 rural communities in Mexico.; Excluded: fasting glucose ≥126 mg/dL, triglycerides concentration ≥400 mg/dL, mmol/L), total cholesterol 239 mg/dL (6.2 mmol/L), blood pressure ≥140/90 mm Hg, renal insufficiency, eating disorders, pregnant or lactating, consumption >3 servings/day of milk or dairy products, treatment for obesity or with metformin, thiazolidinediones, or hormones within past 3 months | Intervention: Low-fat milk (LFM): 250 mL LFM 3 times/day + energy-restricted diet (− 500 kcal/day based on body weight at baseline using Harris-Benedict equation). Energy reduction was equal in each study group. No other dairy products were allowed in the diet. (n = 43); Study purpose: to evaluate the effect of the intake of low-fat milk and low-fat milk with added micronutrients on anthropometrics, body composition, blood glucose levels, lipids profile, C-reactive protein, and blood pressure of women following an energy-restricted diet; Other interventions: Low-fat milk with added micronutrients (LFM+M): 250 mL LFM+M 3 times/day + energy-restricted diet. Added micronutrients included iron, magnesium, vitamin E, niacin, folic acid, thiamin, vitamin B-6, and vitamin B-12.; Comparator: Control (CON): energy-restricted diet (−500 kcal/day based on body weight at baseline using Harris-Benedict equation) with no intake of milk or any other dairy product throughout the study duration. (n = 41); Duration: 16wk; Compliance: Adherence logs completed by participants. Compliance measured by dietetics practitioners during home visits 2 times/wk. Participants were asked to return empty milk containers. Adherence to LFM intervention: 96% ± 6%; Adherence to energy-restricted diet: LFM group: 93%; CON: 90%; Outcomes and assessment methods:; - Height, weight, waist circumference: valid measure by study staff Percent body fat, body fat content (kg), fat free mass: measured by DXA; - Baseline, 16 wk | [underlined: ΔWaist circumference, cm], mean (95% CI), intention to treat; Between group, adjusted change (age, initial value, and community random effect), LSD:; LFM: −10.1 (−11.7, −8.4); CON: −9.9 (−11.5, −8.2), p=NS; [underlined: ΔBody fat (%)], mean (95% CI), study completers; Between group, adjusted change (age, initial value, and community random effect), LSD:; LFM: −1.8 (−2.3, −1.3); CON: −1.6 (−2.2, −1.0), p=NS; [underlined: ΔLean body mass, kg], mean (95% CI), study completers; Between group, adjusted change (age, initial value, and community random effect), LSD:; LFM: −1.1 (−1.6, −0.6); CON: −1.1 (−1.7, −0.6), p=NS; [underlined: ΔFat free mass, kg], mean (95% CI), study completers; Between group, adjusted change (age, initial value, and community random effect), LSD:; LFM: −1.1 (−1.6, −0.6); CON: −1.2 (−1.7, −0.6), p=NS; [underlined: ΔBody weight, kg], mean (95% CI), intention to treat; Between group, adjusted change (age, initial value, and community random effect), LSD:; LFM: −3.6 (−4.7, −2.6); CON: −3.2 (−4.3, −2.2), p=NS; ΔBMI, kg/m^2^, mean (95% CI), intention to treat; Between group, adjusted change (age, initial value, and community random effect), LSD:; LFM: −1.5 (−2.0, −1.1); CON: −1.4 (−1.9, −0.9), p=NS | Model adjustments:; - TEI: yes, all participants followed an energy-restricted diet (−500 kcal/day based on body weight at baseline using Harris-Benedict equation). Energy reduction was equal in each study group.; - Other:; Limitations:; - Differences in attrition; Not sufficiently powered; No preregistered data analysis plan; Funding:; Instituto de Nutrición Lala
Ting, 2007 ^50^; RCT-Parallel, Follow-up of Chee 2003, Malaysia; Baseline N=200, Analytic N=139 (Attrition: 31%); Power: NR; Participant characteristics at baseline: postmenopausal women; - Age: Mean ~59y at baseline (55–70y at follow-up); - Female: 100%; - Race/ethnicity: 100% Chinese; - SEP: NR; - Anthropometry: BMI, Mean ~24 kg/m2; - Physical activity: “physical activity scores”, Mean (SD), Control 101 (53), Milk 102 (52); - Smoking: NR; - Diet quality: NR; - TEI: Mean (SD), Control 1552 (290) kcal/d, Milk 1569 (288) kcal/d; Study beverage intake at baseline:; Control: 56% drank some amount of milk; 60% skimmed milk, 35% low-fat milk, 5% full cream milk; Milk group: 85% drank some amount of milk; 48% drank <1 glass/d and 32% drank 1–2 glasses/d; 76% skimmed milk, 18% low fat milk, and 6% full cream milk; Included: healthy, ambulatory Chinese women aged 50–65y and >5y postmenopausal; no disease or use of medications known to affect calcium and bone metabolism.; Excluded: Women taking calcium supplements (>500 mg/day) for >1 mo, drinking ≥2 or more glasses of milk/d at baseline, receiving treatment for osteoporosis, had severe illness, moved or were unable to be contacted, or did not consent to participate further. | Intervention: High calcium skimmed milk (50g powder reconstituted with 400mL water/day); asked to maintain usual physical activity and dietary patterns; given advice to adjust energy intake to compensate for additional calories provided by milk, n=75; Study purpose: to determine if the effectiveness of a milk supplementation intervention (compared to usual diet control) was sustained 18mo after RCT conclusion; Other interventions: none; Comparator: Control: asked to maintain usual milk consumption (<2 glasses/d), physical activity, and dietary patterns, n=64; Duration: 24mo; Compliance: 85% of participants who were given milk supplements previously had voluntarily continued habit of drinking 1–2 glasses of milk almost daily; Outcomes and assessment methods:; - Height and weight measured by study personnel; used to calculate BMI; Lean body mass measured by DXA Body fat percentage measured by DXA; - At baseline, 24mo (end of supplementation), and 45mo follow-up (~21mo after supplement withdrawal) | Per protocol analyses; [underlined: Body fat (kg)], ANOVA repeated measures, Mean (SD); Baseline, 24mo, 45mo; Control (n=64): 20.8 (8.2), 21.3 (7.5), 22.1 (7.4); Milk (n=75): 19.8 (6.0), 20.4 (6.2), 20.7 (6.5); Change over time, within group: significant increase at 45mo for control group; Change over time, between groups: NS; [underlined: Lean body mass (kg)], ANOVA repeated measures, Mean (SD); Baseline, 24mo, 45mo; Control (n=64): 32.9 (3.8), 31.3 (3.5), 31.4 (3.1); Milk (n=75): 32.8 (4.3), 33.4 (3.8), 33.4 (3.7); Change over time, within group: significant loss at 24mo and 45mo for control group; Change over time, between groups: p<0.005 at 24mo and 45mo; Per protocol analyses; [underlined: Weight (kg)], ANOVA repeated measures, Mean (SD); Baseline, 24mo, 45mo; Control (n=64): 57.0 (9.7), 57.1 (9.5), 57.5 (10.1); Milk (n=75): 56.2 (8.6), 56.7 (8.9), 56.4 (9.2); Change over time, within group: NS; Change over time, between groups: NS; BMI, kg/m^2^, ANOVA repeated measures, Mean (SD); Baseline, 24mo, 45mo; Control (n=64): 24.1 (3.8), 24.2 (3.7), 24.4 (4.0); Milk (n=75): 23.8 (3.5), 23.8 (3.5), 23.8 (3.8); Change over time, within group: NS; Change over time, between groups: NS | Model adjustments:; - TEI: yes (given advnice to adjust EI to compensate for milk); - Other: N/A; Limitations:; - Methods for randomization and concealment NR; Differences in attrition; No power calculation; No preregistered data analysis plan; Funding:; New Zealand Milk (Auckland, New Zealand)
Wagner, 2007 ^51^; RCT-Parallel, U.S.; Baseline N=84, Analytic N=58 (Attrition: 31%); Power: Power: 0.999 for n=12 per group; Participant characteristics at baseline: Adults: premenopausal women with overweight or obesity; - Age: Mean: ~37y; - Female: 100%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Mean BMI: ~33 kg/m2 (Range=26–41); Weight: ~198 lbs; - Physical activity: 3x/wk for 45 min to 1 hr as part of intervention; - Smoking: Non-smoker: 100%; - Diet quality: NR; - TEI: Mean ~1415 kcal/d (500 kcal restriction as part of intervention); Study beverage intake at baseline: Milk group: 20 oz/d of 1% fat milk provided (participants told they would be given either milk or non-dairy milk-like placebo; milk provided weekly in non-labeled plastic container); Exclude: BMI <26, pregnancy, fasting serum glucose >100mg/dL, smoking, irregular menses, health problems that influenced tendence to gain/lose weight, alcohol >1 serv/d, medications that interfere with bone turnover, nutrient absorption, metabolism, excretion, or gastric motility (ie contraceptives, corticosteroids, hormone replacements, acetaminophen, salicylates, and diuretics) | Intervention: 1% milk (20 oz/d provided; energy intake decreased to account for addition of milk), n=17; 12 wk, double-blind RCT; all participants advised to consume 500kcal energy deficit and exercise 45–60 mins, 3 times/wk, supervised; Study duration: to examine the effects of calcium intake on body weight, body fat, and markers of bone turnover in pre-menopausal adult women undergoing a 12 week weight loss program of diet and exercise; Other interventions: Calcium lactate supplement, calcium phosphate supplement; Comparator: Placebo (consumed enough dairy from milk, yogurt, and cheese to produce a dietary intake of 750 mg of daily calcium), n=13; Duration: 12wk; Compliance: Monitored by dietitian via daily food records; Outcomes and assessment methods:; - Body weight measured; - Body composition determined using bioelectrical impedance; - Baseline, weekly for 12wk | Per protocol analyses; [underlined: Body Fat], Paired t-test and ANOVA; Change over time, within group: Placebo: P<0.01, Data NR; Milk: P<0.01, Data NR; Change over time, between groups: Placebo vs Milk group: milk group lost less fat than placebo, Data NR, P<0.05; [underlined: Weight], Paired t-test and ANOVA; Change over time, within group: 0wk, 12wk; Placebo: P<0.01, Data NR Milk: P<0.01, Data NR; Change over time, between groups: Placebo vs Milk group: P=NS, Data NR | Model adjustments:; - TEI: yes; - Other: N/A; Limitations:; N/A• Randomization technique and allocation concealment not clear; Funding:; Purac of America, Inc.
Prospective cohort studies
Babio, 2015 ^52^; PCS, PREDIMED, Spain; Analytic N=1,386; Participant characteristics at baseline:; Adults; - Age: ~67y; Range, Men: 55–80y; Women: 60–80y; - Female: 52%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI: Mean ~28.4; WC (women): Mean ~92.4 cm; WC (men): Mean ~97.9 cm; Abdominal obesity: 44%; - Physical activity: Mean~274 METxmin/d; - Smoking: Former: 26%; Current: 16%; - Diet quality: Food group intake, Mean (SD); Vegetables: ~342 (123) g/d; Fruit: ~390 (150) g/d; - TEI: Mean~2323 kcal/d; Study beverage intake at baseline: Total milk: Mean~263 g/d; Median=207 g/d; Low-fat milk: Mean~230 g/d; Whole-fat milk: Mean~39 g/d; Include: either T2D or ≥3 CVD risk factors (hypertension, high plasma LDL, low plasma HDL, overweight or obesity, current smoking, or family history of premature CHD; Exclude: CVD; dietary data collected after the development of MetS | Exposure: Total dairy milk; Low-fat milk (skim, 1%, & 2%); Whole milk; Other exposures:; Comparator: Categorical intake (tertiles); Outcomes and assessment methods:; - Waist circumference measured by trained staff; abdominal obesity defined as waist circumference ≥88 cm in women and ≥102 cm in men; - At baseline, yearly during follow-up, follow-up varied 1 – 7y (baseline: 2003–09; end of follow-up: 2010) | [underlined: Abdominal obesity], by average total milk intake, HR (95% CI), Cox regression; Total dairy milk: Tertile 1: REF; Tertile 2: 1.02 (0.83, 1.26); Tertile 3: 1.08 (0.86, 1.36); P-trend=0.49; [underlined: Low-fat dairy milk]: Tertile 1: REF; Tertile 2: 1.11 (0.89, 1.33); Tertile 3: 0.96 (0.78, 1.18); P-trend=0.66; [underlined: Whole-fat dairy milk]: Tertile 1: REF; Tertile 2: 0.87 (0.71, 1.08); Tertile 3: 0.97 (0.78, 1.19); P-trend=0.91 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking, diet quality; - Other: Medications, alcohol, consumption of vegetables, fruit, legumes, cereals, fish, red meat, biscuits, olive oil, and nuts, intervention group; Limitations:; - Did not account for key confounders: race/ethnicity, SEP; - Not all key confounders accounted for; Start of follow-up and exposure do not coincide; No information on non-completers; No a priori analysis plan for this secondary analysis; Funding:; Spanish Ministry of Health; Thematic Network; European Regional Development Fund; Catalan Nutrition Center of the Institute of Catalan Studies
Bes-Rastrollo, 2008 ^53^; PCS, Nurses’ Health Study II, US; Analytic N=50,026; Participant characteristics at baseline:; Female nurses; - Age: Mean (SD): 36.5y (4.6); - Female: 100%; - Race/ethnicity: NR; - SEP: 100% nurses; - Anthropometry: Mean (SD): BMI: 24.2 (5.0); Weight, kg: 65.9 (14.3); - Physical activity: MET-h/wk, Mean (SD): 20.4 (26.4); - Smoking: Current: 11%; - Diet quality: Dietary ED, kcal/g (food only): 1.2 (0.4); Dietary ED, kcal/g (food+bevs): 1.1 (0.3); Food group intake, Mean (SD):; Vegetables, g/d: 159 (99); Fruit, g/d: 176 (118); Other macronutrient and food group intakes reported in paper; - TEI: Mean (SD), kcal/d 1771 (522); Study beverage intake at baseline: NR; Exclude: missing dietary (completely missing or >9 missing items), physical activity, weight, or follow-up data; unreasonable energy intakes; history of diabetes or CVD; cancer; pregnancy | Exposure: Average intake across surveys for total milk and skim milk; Baseline FFQ categories: skim or low-fat milk, whole milk; 2nd follow-up FFQ categories: skim or 1%, 2%, whole milk, soy milk; 1 serving = 8oz.; Other exposures: SSB, LNCSB, juice, coffee, tea; Comparator: Categorical intake (tertiles); Outcomes and assessment methods:; - Self-reported; - Baseline, 8y | [underlined: Weight change over 8y, kg], Linear regression; [underlined: Skim milk]: Lowest tertile of change in intake over 8y (ref) vs Highest tertile: Data NR, P=NS; [underlined: Total milk]: Lowest tertile of change in intake over 8y (ref) vs Highest tertile: Data NR, P=NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, anthropometry at baseline, physical activity, smoking; - Other: Postmenopausal hormone use, oral contraceptive use; Limitations:; - Did not account for key confounders: race/ethnicity, SEP, diet quality; - Not all key confounders accounted for; Exposures not well defined and FFQ varied over time; No info on non-completers; Self-reported weight; No preregistered data analysis plan; Funding:; NIH; Spanish Ministry of Education; Fundacion Caja Madrid; Amigos de la Universidad de Navarra; AHA Established Investigator Award
Beydoun, 2018 ^54^; PCS, Healthy Aging in Neighborhoods of Diversity across the Life Span (HANDLS), US; Analytic N=1,371; Participant characteristics at baseline: Adults, self-identify as African-American or White, urban setting; - Age: Mean (SE): 48.4y (0.24); - Female: 59%; - Race/ethnicity: African-American: 59%; White: 41%; - SEP: Above poverty, 60.1%; Education: <HS: 6.8%, HS: 56.6%, >HS: 36.6%; - Anthropometry: BMI ≥30, 42.1%; Central obesity, 59.8%; - Physical activity: NR; - Smoking: Current: 41%; - Diet quality: Food group intake, serv/d, Mean (SE); Fruit: 0.73 (0.03); Dark green veg: 0.12 (0.01); Orange veg: 0.07 (0.00); - TEI: Mean (SE): 2003 (26) kcal/d; Study beverage intake at baseline: Mean (SE):; Total milk (svg/d): 0.51 (0.02); Total milk (g/d): 64.3 (2.9); Whole milk (g/d): 32.4 (2.2); Low fat/fat free milk (g/d): 31.8 (2.2); Intake data stratified by sex and race provided in paper; Include: age 30–64y, self-identify as African-American or White, perform ≥5 study measures, present valid picture identification; Exclude: pregnancy, recent cancer treatment, multiethnic | Exposure: Total dairy milk (whole and reduced fat), analyzed as total dairy milk intake; Other exposures: N/A; Comparator: Continuous intake; Outcomes and assessment methods:; - Measured by study personnel; - Baseline, 5y | [underlined: Incident central obesity], HR (95% CI), Cox proportional hazards regression; Per svg/d increase in baseline or average annual change in milk intake; [underlined: All participants (N=588)] Baseline: 1.00 (0.75, 1.36); Change: 1.01 (0.75, 1.36); [underlined: Men]; Baseline: 0.89 (0.79, 0.99); Change: 0.82 (0.50, 1.32); [underlined: Women]; Baseline: 1.07 (0.94, 1.21); Change: 0.97 (0.60, 1.57); [underlined: White]; Baseline: 1.14 (1.00, 1.29); Change: 1.10 (0.69, 1.76); [underlined: African-American]; Baseline: 0.87 ( 0.75, 1.00); Change: 0.76 (0.44, 1.34); [underlined: Incident obesity], HR (95% CI), Cox proportional hazards regression; Per svg/d increase in baseline or average annual change in milk intake:; [underlined: All participants (N=859)]; Baseline: 0.98 (0.90, 1.06); Change: 0.76 (0.51, 1.15); [underlined: Men]; Baseline: 0.94 (0.81, 1.10); Change: 0.61 (0.31, 1.21); [underlined: Women]; Baseline: 1.05 (0.91, 1.22); Change: 1.00 (0.53, 1.88); [underlined: White]; Baseline: 0.92 (0.79, 1.06); Change: 0.59 (0.32, 1.08); [underlined: African-American]; Baseline: 1.14 (0.98, 1.34); Change: 1.24 (0.64, 2.45) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race/ethnicity, SES, smoking, diet quality; - Other: Alcohol, current drug use, self-rated health, total fruit, dark green vegetables, deep yellow vegetables, whole grains, non-whole grains, legumes, nuts/seeds, soy, total meat/poultry/fish, eggs, discretionary solid fat, discretionary oils, added sugars, caffeine; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity; - Not all key confounders accounted for; No info on non-completers; No preregistered data analysis plan; Funding:; Intramural Research Program NIH/NIA
Chen, 2009 ^55^; PCS, PREMIER Study, U.S.; Analytic N=810; Participant characteristics at baseline: Adults enrolled in an 18mo behavioral intervention trial to lower BP; - Age: Mean (SD): 50 (9)y; - Female: 62%; - Race/ethnicity: Black: 34.4%; Non-Hispanic White: 64.2%; Other: 1.4%; - SEP: Education, college degree or above: 57%; Annual household income >$45,000/y, 70.0%; - Anthropometry: Mean (SD), Weight: 95.2 (18.8) kg; BMI, 33.1 (5.8) kg/m2;; Obesity (BMI ≥ 30 kg/m2): 65%; - Physical activity: Mean (SD), 130.5 (14.5) heart rate/min; Estimated energy expenditure, 33.7 (2.9) kcal·kg-1·d-1; - Smoking: Current smoker: 5%; - Diet quality: SSB Mean (SD): 311 (355) mL/d; - TEI: ~1,874 kcal/d; Study beverage intake at baseline: Milk intake at baseline, Mean (SD), 94.6 (183.3) mL/d; Include: adults with prehypertension or stage 1 hypertension; Exclude: antihypertensive, weight-loss, or oral steroid medications; diabetes; history of cardiovascular event; CHF; current symptoms of angina or peripheral vascular disease; cancer in past 2y; renal insufficiency; psychiatric hospitalization in past 2y | Exposure: Dairy milk (whole milk, 2% reduced-fat milk, 1% low-fat milk, and skim milk), analyzed as total milk intake; Other exposures: 100% juice, SSB, LNCSB, Coffee/Tea; Comparator: Continuous intake; Outcomes and assessment methods:; - Weight measured using calibrated scale; - Baseline, 6mo, 18mo follow up | [underlined: Weight (kg)], β (95% CI); Change over time by change in milk intake:; 6mo: 0.16 (−0.27, 0.60), P=0.48; 18mo: 0.11 (−0.76, 1.03), P=0.79 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race and/or ethnicity, SEP, anthropometry at baseline, physical activity, smoking, diet quality (other beverage types); - Other: Energy density; medications; alcohol; intervention group, changes in other beverages, fat intake, carbohydrate intake; Limitations:; - Did not account for key confounders: none; - No preregistered data analysis plan; Funding:; NHLBI; Center for Human Nutrition, Johns Hopkins Bloomberg School of Public Health; NICHD
Drapeau, 2004 ^56^; PCS, Quebec Family Study, Canada; Analytic N=248; Participant characteristics at baseline:; Parents and adult offspring; - Age: Mean (SEM): 39.6y (0.9), Range: 18–65y; - Female: 55%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: BMI, Mean (SEM): 25.3 (0.3), Range: 17.4–55.6; - Physical activity: NR; - Smoking: NR; - Diet quality: Macro- and micronutrient intakes reported in paper; - TEI: NR; Study beverage intake at baseline: NR; Exclude: missing any dietary data; responding "I don’t know" to any dietary intake category | Exposure: Low-fat milk (skimmed and partly skimmed), whole dairy milk (likely dairy only, but does not specify); Other exposures: SSB, juice; Comparator: Continuous intake; Outcomes and assessment methods:; - Weight, waist circumference, sum of 6 skinfold thicknesses (triceps, biceps, medial calf, subscapular, suprailiac, and abdominal) measured by study personnel Body fat percentage estimated using underwater weighing; - Baseline, 6y | [underlined: Body fat percentage], change over 6y, Linear regression; Low-fat milk change in intake over 6y: NS, Data NR; Whole milk change in intake over 6y: NS, Data NR; [underlined: Waist circumference], change over 6y, Linear regression; Low-fat milk change in intake over 6y: NS, Data NR; Whole milk change in intake over 6y: NS, Data NR; [underlined: Sum of 6 skinfold thicknesses], change over 6y, Linear regression; Low-fat milk change in intake over 6y: NS, Data NR; Whole milk change in intake over 6y: NS, Data NR; [underlined: Weight change over 6y], Linear regression; Low-fat milk change in intake over 6y: NS, Data NR; Whole milk change in intake over 6y: NS, Data NR | Model adjustments:; - TEI: no; - Key confounders: age, anthropometry at baseline, physical activity; - Other:; Limitations:; - Did not account for key confounders: sex, race/ethnicity, SES, smoking, diet quality; - Did not account for all key confounders; Validation of 3-day dietary record unclear; No information on non-completers; No preregistered data analysis plan; Funding:; Canadian Institutes of Health Research
Duffey, 2010 ^57^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA) Study, U.S. Analytic N=2,444; Participant characteristics at baseline: adults; - Age: Mean (SD): 25.0 y (3.6); - Female: 54%; - Race/ethnicity: Black: 47.4%; White: 52.6%; - SEP: NR; - Anthropometry: Mean (SD); BMI: 24.5 (5.0) kg/m2; WC: 77.3 cm (10.9); - Physical activity: Mean (SD): 429 exercise units/wk (302); - Smoking: Current 28.1%, Former 13.1%, Never 58.7%; - Diet quality: NR; - TEI: NR; energy from food, Mean: 2347 kcal; Study beverage intake at baseline: Low-fat milk: 61% consuming; among consumers: Mean=160 kcal/d, SE=4; Whole-fat milk: 47% consuming; among consumers: Mean=204 kcal/d, SE=6; Included in original cohort: age between 18–30 at baseline; White or Black race; permanent residence in one of 4 recruitment sites (Birmingham, AL, Chicago, IL, Minneapolis, MN, Oakland, CA); free of a long-term disease or disability that would interfere substantially with any part of the examination ("Thus, persons who were blind, deaf, mute, mentally retarded, or unable to walk on a treadmill were excluded."); Excluded from original cohort: pregnant or up to 3 months post-partum; Excluded from current analyses: people with a high WC at baseline or year 7 | Exposure: Low-fat milk (skim and ≤2% fat), Whole-fat milk (≥3% fat); no information on sweetener content; Other exposures: 100% juice, SSB; Comparator: Low-fat milk intake (continuous; kcal/d); Low-fat milk intake (categorical; quartiles); Whole-fat milk intake (continuous; kcal/d); Whole-fat milk intake (categorical; quartiles); Outcomes and assessment methods:; - WC at minimum abdominal girth measured in duplicate; High WC defined as WC>88cm (women) or >102cm (men); - Baseline, 20y follow-up | Milk intake, categorical; [underlined: High WC], Poisson regression, RR (95% CI); Low-fat milk: 1.02 (0.95, 1.08), P for trend = 0.639; Whole-fat milk: 1.06 (0.98, 1.13), P for trend = 0.143; Milk intake, continuous; [underlined: High WC], Poisson regression, RR (95% CI); Low-fat milk: 1.02 (0.97, 1.07); Whole-fat milk intake: 1.02 (0.98, 1.07) | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, anthropometry at basleine (body weight), physical activity, diet quality, smoking; - Other: Calories from alcohol, CARDIA exam center; Limitations:; - Did not account for key confounders: socioeconomic position, anthropometry at baseline (WC); - Unclear if exposure assessment tool is validated; High missing data; No preregistered data analysis plan; not all key confounders accounted for; Funding:; Danone Research Center; NIH; UNC-CH Center for Environmental Health and Susceptibility; UNC-CH Clinic Nutrition Research Center; Carolina Population Center; University of Alabama at Birmingham Coordinating Center; University of Alabama at Birmingham Field Center, University of Minnesota Field Center, Northwestern University Field Center, Kaiser Foundation Research Institute
Funtikova, 2015^58^; PCS, Spain; Analytic N=2,112; Participant characteristics at baseline: adults; - Age: Mean: ~49.2y; - Female: 53%; - Race/ethnicity: NR; - SEP: Higher education ~37%; - Anthropometry: Mean: WC, ~89.6 cm; - Physical activity: Mean: ~200 MET-min/d (leisure time); - Smoking: Current smoker ~26%; - Diet quality: validated, modified Mediterranean Diet Score (mMDS): ~17.5 (out of a possible 30); - TEI: Mean: ~11.2 MJ/d kcal/d; Study beverage intake at baseline: Whole milk, mL/d, mean (SD): 63 (131); no consumption: 66%, <1 svg/d: 13%, ≥1 svg/d: 21%; Skim and low-fat milk, mL/d, mean (SD): 115 (178); no consumption: 54%, <1 svg/d: 12%, ≥1 svg/d: 34%; Included in original cohort (n=3058): adults aged 25–75y residing in Girona, Spain; Excluded from current analyses: no longer residing in catchment area (n=343); lost to follow-up (n=534), missing data for WC (n=37) and smoking status (n=32) | Exposure: Whole milk (4% fat), Skim and Low-fat milk (1 svg = 200mL); no information on sweetener content; Other exposures: SSB, 100% juice; Comparator: Whole milk intake (continuous; 100 kcal/d); Whole milk intake (categorical; svg/d); No consumption (ref), <1, ≥1; Whole milk intake change (categorical); No consumption (ref), Decrease, Increase, Maintain; Skim and low-fat milk intake (continuous; 100 kcal/d); Skim and low-fat milk intake (categorical; svg/d); No consumption (ref), <1, ≥1; Skim and low-fat milk intake change (categorical); No consumption (ref), Decrease, Increase, Maintain; Outcomes and assessment methods:; - WC measured midway between lowest rib and iliac crest with participant lying horizontally. Abdominal obesity defined as >102 cm for men and >88 cm for women; - Baseline, 9y follow-up | Whole milk, continuous; [underlined: WC, cm], Change per 100 kcal/d increase, Mean (95% CI), linear regression: −0.19 (−0.66, 0.28), P=0.42; Men: −0.38 (−1.02, 0.26), P=0.25; Women: 0.06 (−0.63, 0.74), P=0.87; Whole milk change, categorical; [underlined: WC, cm], Change in WC by change in consumption, Mean (95% CI), linear regression:; [underlined: Full sample]; No consumption (ref); Decrease: −0.03 (−1.00, 0.94), P=0.95; Increase: −0.26 (−1.56, 1.04), P=0.69; Maintain: −0.68 (−2.05, 0.70), P=0.33; [underlined: Men (n=1000)]; No consumption (ref); Decrease: −1.13 (−2.39, 0.13), P=0.08; Increase: −1.69 (−3.27, −0.12), P=0.036; Maintain: −1.56 (−3.22, 0.09), P=0.06; [underlined: Women (n=1112)]; No consumption (ref); Decrease: 1.05 (−0.41, 2.51), P=0.16; Increase: 1.46 (−0.64, 3.57), P=0.17; Maintain: 0.35 (−1.92, 2.61), P=0.77; Whole milk, categorical; [underlined: Abdominal obesity], OR (95% CI), logistic regression; Incidence by baseline intake:; [underlined: Full sample]; No consumption (ref); <1 svg/d: 1.58 (1.07, 2.32); ≥1 svg/d: 1.00 (0.72, 1.40); [underlined: Men (n=756)]; No consumption (ref); <1 svg/d: 1.32 (0.74, 2.38); ≥1 svg/d: 1.25 (0.75, 2.08); P for trend=0.34; [underlined: Women (n=723)]; No consumption (ref); <1 svg/d: 1.90 (1.13, 3.20); ≥1 svg/d: 1.21 (0.78, 1.88); P for trend=0.20; Skim and low-fat milk, continuous; WC, cm, Mean (95% CI), linear regression; Change per 100 kcal/d increase:; 0.25 (−0.30, 0.79), P=0.37; Men: 0.27 (−0.55, 1.08), P=0.52; Women: 0.30 (−0.45, 1.04), P=0.44; Skim and low-fat milk change, categorical; [underlined: WC, cm], Change by change in consumption, Mean (95% CI), linear regression:; [underlined: Full sample]; No consumption (ref); Decrease: 0.39 (−0.68, 1.47), P=0.47; Increase: 0.40 (−0.64, 1.43), P=0..45; Maintain: 0.31 (−0.73, 1.35), P=0.56; [underlined: Men (n=1000)]; No consumption (ref); Decrease: 0.49 (−0.92, 1.90), P=0.52; Increase: 0.12 (−1.18, 1.42), P=0.42; Maintain: 0.33 (−1.18, 1.83), P=0.58; [underlined: Women (n=1112)]; No consumption (ref); Decrease: 0.40 (−1.21, 2.01), P=0.47; Increase: 0.74 (−0.89, 2.37), P=0.45; Maintain: 0.42 (−1.07, 1.91), P=0.56; Skim and low-fat milk, categorical; [underlined: Abdominal obesity], OR (95% CI), logistic regression; Incidence by baseline intake:; [underlined: Full sample]; No consumption (ref); <1 svg/d: 0.76 (0.49, 1.18); ≥1 svg/d: 0.94 (0.69, 1.27); [underlined: Men (n=756)]; No consumption (ref); <1 svg/d: 0.67 (0.35, 1.31); ≥1 svg/d: 0.77 (0.46, 1.28); P for trend=0.18; [underlined: Women (n=723)]; No consumption (ref); <1 svg/d: 0.85 (0.47, 1.54) AQ18; ≥1 svg/d: 0.95 (0.66, 1.35); P for trend=0.69 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Other: energy under- or over-reporting; Limitations:; - Did not account for key confounders: race and/or ethnicity; - High attrition with no information on non-completers; No preregistered data analysis plan; Not all key confounders accounted for; Funding:; Catalan Government; Carlos III Health Institute European Fund for Regional Development; Catalonian Agency for the Administration of University and Research Grants
Guerendiain, 2018^59^; PCS, Ecuador; Analytic N=31; Participant characteristics at baseline: adults; - Age: Mean (SD): 39 y (7.5); - Female: 81%; - Race/ethnicity: NR; - SEP: Occupation, Academics 40.58%, Administrative 59.42 %; - Anthropometry: BMI, Mean~26.3 kg/m2; - Physical activity: <150 min/wk moderate-vigorous exercise (inclusion criteria); randomized to Zumba or Zumba and resistance exercise; - Smoking: NR; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: Milk intake (g/d), tertiles: T1: ≤133.33, T2: 133.34–250.00, T3: >250.00; Included: adults not meeting current minimum physical activity WHO guidelines (i.e., engaging in less than 150 min of moderate to vigorous physical activity per week) and inexperienced at Zumba Fitness classes; Excluded: serious illness such as cancer, current skeletal muscle injury or chronic medical conditions such as diabetes or CVD, dropout (n=15), did not correctly complete evaluations (n=10), did not attend follow-up visit (n=5) | Exposure: Milk, no information on % fat or sweetener content.; Other exposures:; Comparator: Milk intake (categorical; tertiles): T1 (≤133.33 g/d), T2 (133.34–250.00 g/d), T3 (>250.00 g/d); Milk intake (continuous; mL/d): Per tertiles of BMI change; Outcomes and assessment methods:; - Height and weight measured by study personnel. Waist and hip perimeters measured by study personnel; waist-hip index calculated from coefficient between waist and hip perimeters using protocol from WHO. Sum of 6 skinfold thickness measured using ISAK procedures. Percentage body fat mass estimated using the Faulkner equation. Muscle mass estimated using methodology of four compartments (De Rose and Guimaraes, 1980); - Baseline, 16-wk follow-up | Milk intake, categorical; [underlined: Sum of 6 skinfolds (mm)], change from 0–16wks by tertile of milk intake at baseline; Mean (SD), linear regression:; T1 (n=8): −36.04 (6.46); T2 (n=12): −25.23 (18.44); T3 (n=11): −38.69 (11.66); P=0.108, d: 0.17 (95% CI: −0.44, 0.78); [underlined: Fat mass (kg)], change from 0–16wks by tertile of milk intake at baseline; Mean (SD), linear regression:; T1 (n=8): −2.78 (0.89); T2 (n=12): −1.91 (1.62); T3 (n=11): −2.98 (1.83); P=0.250, d: 0.13 (95% CI: −0.84, 1.10); [underlined: Fat mass (%)], change from 0–16wks by tertile of milk intake at baseline; Mean (SD), linear regression:; T1 (n=8): −4.06 (1.12); T2 (n=12): −2.91 (2.28); T3 (n=11): −3.97 (1.41); P=0.214, d: −0.05 (95% CI: −0.77, 0.67); [underlined: Muscle mass (kg)], change from 0–16wks by tertile of milk intake at baseline; Mean (SD), linear regression:; T1 (n=8): 2.36 (1.29); T2 (n=12): 1.85 (1.25); T3 (n=11): 2.97 (1.92); P=0.105, d: −0.37 (95% CI: −1.38, 0.63); [underlined: Muscle mass (%)], change from 0–16wks by tertile of milk intake at baseline; Mean (SD), linear regression:; T1 (n=8): 4.10 (3.05); T2 (n=12): 3.05 (2.17); T3 (n=11): 4.15 (1.40); P=0.211, d: −0.03 (95% CI: −0.76, 0.70); [underlined: Waist-hip index], change from 0–16wks by tertile of milk intake at baseline; Mean (SD), linear regression:; T1 (n=8): −0.00 (0.05); T2 (n=12): 0.00 (0.03); T3 (n=11): 0.00 (0.02); P=0.847, d: −0.13 (95% CI: −1.03, 0.77); Milk intake, categorical; [underlined: Weight (kg)], change from 0-16wks by tertile of milk intake at baseline; Mean (SD), linear regression; T1 (n=8): −0.65 (1.68); T2 (n=12): −0.21 (1.45); T3 (n=11): −0.25 (2.95); P=0.918, d: −0.18 (95% CI: −1.33, 0.96); BMI (kg/m^2^), change from 0-16wks by tertile of milk intake at baseline; Mean (SD), linear regression; T1 (n=8): −0.23 (0.64); T2 (n=12): −0.09 (0.88); T3 (n=11): 0.25 (1.49); P=0.585, d: −0.37 (95% CI: −1.28, 0.54 | Model adjustments:; - TEI: no; - Key confounders: physical activity; - Other:; Limitations:; - Did not account for key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Not all key confounders accounted for; Three day dietary record used to assess milk intake; Participants underwent nutrition education and physical activity “co-exposure”; Attrition 48% without information on non-completers; No preregistered data analysis plan; Funding:; National University of Chimborazo; University of Granada Plan Propio de Investigacion 2016
Guo, 2018 ^60^; PCS, Caerphilly prospective cohort study (CAPs), UK; Analytic N=1,690; Participant characteristics at baseline:; Adult men; - Age: Mean: ~52y; - Female: 0%; - Race/ethnicity: NR; - SEP: Manual workers, ~64%; - Anthropometry: BMI, Mean~26.3; - Physical activity: Leisure activity, ~48%; - Smoking: Current ~52%; - Diet quality: Fiber (cereal sources): ~7.8 g/day; Fiber (vegetable sources): ~8.5 g/day; Fruit: ~5.1 times/week; Vegetable: ~9.4 times/week; Fish: ~0.9 times/week; Sugar, g/day, mean (SD): Q1: 81.9 (32.8), Q2: 91.2 (34.1), Q3: 93.0 (31.2), Q4: 110.7 (41.2); p<0.001; Red meat, times/week, mean (SD): Q1: 5.2 (2.5), Q2: 5.5 (2.9), Q3: 5.4 (2.6), Q4: 5.9 (2.9); p=0.001; Eggs, n/week, mean (SD): Q1: 3.5 (2.5), Q2: 3.8 (2.2), Q3: 3.8 (2.6), Q4: 4.7 (5.4); p<0.001; - TEI: Mean: ~9.6 MJ/d; Study beverage intake at baseline: Milk, Mean: ~297.9 g/d; Included: men aged 45–59y at baseline, living in Caerphilly (Wales, UK) and surrounding villages; Excluded: lost to follow-up (n=561), previous diagnosis of CVD, diabetes, and/or cancer (n=101), missing data on confounders (n=160) | Exposure: Milk, no information on % fat or sweetener content.; Other exposures:; Comparator: Milk intake (categorical; quartiles): Q1 (0 g/d), Q2 (0 – 293 g/d), Q3 (294 – 585 g/d), Q4 (> 585 g/d); Outcomes and assessment methods:; - Weight and height measured by study personnel; - Baseline, 5y follow-up, 10y follow-up | BMI, kg/m^2^, Change based on milk intake quartiles at baseline; Mean (SE), linear regression; [underlined: At 5y]:; Q1 (n=92; ref); Q2 (n=773): 0.135 (0.164); Q3 (n=687): 0.041 (0.166); Q4 (n=110): 0.106 (0.213); P for trend, 0.664; [underlined: At 10y]:; Q1 (n=68; ref); Q2 (n=648): 0.133 (0.240); Q3 (n=595): −0.053 (0.243); Q4 (n=93): 0.203 (0.307); P for trend, 0.523 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline (BMI), physical activity, diet quality, smoking; - Other: Alcohol intake, incident diabetes, cancer, hypertension and CVD during 10-year follow-up; Limitations:; - Did not account for key confounders: race and/or ethnicity; - Not all key confounders accounted for; Start of follow-up and exposure do not coincide (Phase 1 n=1951; Phase 2 (5y later) n=447); Attrition 30% and information on non-completers not reported; No preregistered data analysis plan; Funding:; No external funding
Hasselbalch, 2010 ^61^; PCS, GEMINAKAR sample within Danish Twin Registry, Denmark; Analytic N=238 twin pairs (for weight change); 192 twin pairs for WC change; Participant characteristics at baseline:; Adult Danish twins; - Age: All information on key confounders is based on the cross-sectional sample, of which the longitudinal sample is a smaller subset; Mean: 38y (range: 18–67y); - Female: 51%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: Baseline BMI: 25.1±3.0 (males); 23.8±3.9 (females); Baseline waist circumference: 90.0±8.6 cm (males); 78.1±10.1 cm (females); - Physical activity: NR; - Smoking: NR; - Diet quality: Baseline dietary energy density: 3.5±0.8 kJ/g (males); 2.9±0.9 kJ/g (females); - TEI: Males: 11.2±3.4 MJ; Females: 8.6±2.2 MJ; Study beverage intake at baseline: Baseline energy from low-fat milk products: 622.1±613.9 kJ (males); 614.3±554.1 kJ (females); Baseline energy from high-fat milk products: 721.7±716.6 kJ (males); 615.3±551.0 kJ (females); Excluded: Dizygotic twin pairs; individuals or pairs with diabetes or CVD, pregnancy, breastfeeding, alcohol/drug abuse or conditions making it difficult to participate in clinical exam | Exposure: High-fat and low-fat milk products analyzed separately; no information on milk fat percentages and unclear what types of products were included in each category. No information on sweetener content.; Other exposures: SSB; Comparator: Different intake of milk (continuous); Outcomes and assessment methods:; - Weight and waist circumference measured by study staff at baseline, self-reported in 2002; - Baseline (1997–2000) and 2002 | [underlined: Waist circumference change], correlation coefficient; Women: "significantly positively associated" with high-fat milk products (data NR).; Men: Data NR; [underlined: BMI change], correlation coefficient Women: "significantly inversely associated" with low-fat milk products (data NR).; Men: Data NR | Model adjustments:; - TEI: yes; - Key confounders: race/ethnicity, sex, age (comparison between MZ twins); physical activity; smoking; anthropometry at baseline; - Other:; Limitations:; - Did not account for key confounders: socioeconomic position, diet quality; - Not all key confounders accounted for; Exposure data only measured at baseline; Weight and waist circumference were self-reported; No preregistered data analysis plan; Funding:; Danish Council for Strategic Research; Danish Medical Research Fund; Danish Diabetes Association; NOVO Foundation; Danish Heart Foundation; Apotekerfonden; European Union Contract; DIOGENES (supported by European Community)
Holmberg, 2013 ^62^; PCS, Sweden; Analytic N=1,238; Participant characteristics at baseline:; Adult men; - Age: Mean (SD): 50.3 (6.0) y; - Female: 0%; - Race/ethnicity: NR; - SEP: Education level, 41.6% Mandatory school, 31.7% Vocational school, 10.7%; Secondary school, 7.1% College, 9.0% University; - Anthropometry: BMI, mean (SD): 26.4 (3.2) kg/m2; Normal weight: 35.6%, Overweight: 50.3%, Obesity: 14.1%; WHR ≥1: 6.5%; - Physical activity: 28.8% sedentary, 56.4% low, 14.8% moderate or vigorous; - Smoking: 23.3% daily smokers; - Diet quality: Fruit intake ≥ once/day: 52.8%; Vegetable intake ≥ once/day: 51.8%; Fruit and vegetables daily: 33.5%; - TEI: NR; Study beverage intake at baseline: Milk type: 48.9% low fat (1.5% fat or less), 51.1% high fat; Included: male farmers born between 1930 and 1949 living in nine selected rural municipalities in Sweden (identified from Swedish National Farm Register); Excluded: central obesity at baseline (n=116) | Exposure: Type of milk normally consumed (non-homogenized farm milk, full fat milk with 3% fat, semi-skimmed with 1.5% fat, skimmed with 0.5% fat). No information on sweetener content.; Other exposures:; Comparator: Type of milk (categorical; fat content): Low fat milk (1.5% fat or less), n=609; High fat milk (full fat milk), n=629; Outcomes and assessment methods:; - Waist circumference measured at level of umbilicus; hip circumference measured at widest part of the hips. Central obesity defined as WHR ≥1; - Baseline, 12y follow-up | [underlined: Incident central obesity (assessed by WHR)], OR (95% CI), logistic regression By milk fat consumed, between groups: Low fat (ref); High fat: 0.64 (0.47, 0.88) | Model adjustments:; - TEI: no; - Key confounders: sex; - Other:; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Not all key confounders accounted for; Dietary assessment not validated; Attrition 47% with no information on those lost to follow-up; No pre-registered data analysis plan; Funding:; AFA Insurance; LRF Research Foundation; Swedish Council for Working Life and Social Research; Kronoberg County Council
Johansson, 2018 ^63^; PCS, Vasterbotten Intervention Programme (VIP), Sweden; Analytic N=27,682; Participant characteristics at baseline: adults; - Age: 29–34y: 8%, 35–44y: 45%, 45–54y: 28%, 55–65y: 18%; - Female: 51%; - Race/ethnicity: NR; - SEP: 31% academic education (highest level); - Anthropometry: Mean: BMI ~25.7 kg/m2; - Physical activity: 17.4% inactive at leisure time; - Smoking: 20% present smoker; - Diet quality: Mean intake, percent of total energy (E%); Total fat: ~36.1%; Saturated fat: ~15.2%; Protein: ~14.9%; Carbohydrate: ~48.2%; Sucrose: ~6.5%; - TEI: NR; Study beverage intake at baseline: Total non-fermented milk, Mean: ~1.2 svg/d; Total fermented milk, Mean: ~0.6 svg/d; Included: Adults ≥30y, in VIP and Northern Sweden Diet Database; Excluded: incomplete food intake recording (≥10% missing data and/or a missing portion indication), extreme (highest and lowest 1%) food intake levels; extreme energy intake (lowest 1% and > 5000 kCal); age < 29 years or >65 years; implausible height (< 130 or > 210 cm) or weight (< 35 kg) values, or BMI < 15; intake of medication to lower serum lipid, blood glucose or blood pressure; diabetes diagnosis; previous hospitalization for myocardial infarction | Exposure: Non-fermented milk, Fermented milk. No information on fat or sweetener content.; Other exposures:; Comparator: Non-fermented milk intake (categorical; quintiles): Q1: Median=0.08 svg/d; Q2: Median=0.58 svg/d; Q3: Median=1.0 svg/d; Q4: Median=1.4 svg/d; Q5: Median=2.5 svg/d; Fermented milk intake (categorical; quintiles): Q1: Median=0.006 svg/d; Q2: Median=0.16 svg/d; Q3: Median=0.36 svg/d; Q4: Median=0.78 svg/d; Q5: Median=1.1 svg/d; Outcomes and assessment methods:; - Height and weight measured by study personnel. Overweight defined as BMI ≥25; - Baseline, 8–12y follow-up | Non-fermented milk, categorical; [underlined: Incident overweight], HR (95% CI), Cox proportional hazards regression; By quintile of intake:; Q1 (ref); Q2: 0.92 (0.80, 1.05); Q3: 0.95 (0.83, 1.09); Q4: 1.00 (0.87, 1.15); Q5: 0.92 (0.79, 1.07); Fermented milk, categorical; [underlined: Incident overweight], HR (95% CI), Cox proportional hazards regression; By quintile of intake: Q1 (ref); Q2: 1.03 (0.90, 1.18); Q3: 0.93 (0.81, 1.07); Q4: 0.91 (0.79, 1.05); Q5: 0.95 (0.82, 1.10 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, socioeconomic position, physical activity, diet quality, smoking; - Other: Quintile of dairy intake, year at follow-up, BMI at follow-up, mean intake of alcohol; Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline; - Start of follow-up and exposure do not coincide; Exposure assessment tool not validated; High attrition (69%) with no information on non-completers; No preregistered data analysis plan; Not all key confounders accounted for; Funding:; Swedish Research Council for Health, Working Life and Welfare; The Swedish Research Council
Kaikkonen, 2015 ^64^; PCS, Young Finns Study, Finland; Analytic N=1,715; Participant characteristics at baseline: adults; - Age: Mean ~31.7y; - Female: 54%; - Race/ethnicity: NR; - SEP: Educational status (1=low to 3=high), Mean ~2.11; Occupational status (1=low to 3=high), Mean~1.9; - Anthropometry: Mean (SD): BMI (women), 24.38 (0.149); BMI (men), 25.64 (0.138); - Physical activity: Leisure-time physical activity (5=low to 15=high), Mean ~9.9; - Smoking: 23% smoker; - Diet quality: Monthly use (portions), mean (SE); Vegetables and fruits: Women: 39.8 (0.53); Men: 32.5 (0.57); Sweets and chocolate: Women: 9.71 (0.25); Men: 8.45 (0.26); Frequency to add salt to food (1=never, 3=always): Women: 1.22 (0.01); Men: 1.28 (0.02); - TEI: NR; Study beverage intake at baseline: Milk (1=low, 3=high), mean (SD): Women: 1.76 (0.03), Men: 2.11 (0.03); Included: participation in Young Finns Study examination beginning in 1980, outcome data at baseline (2001 in this study) and at follow-up (2007); Excluded: women who were pregnant in either 2001 or 2007 or had missing pregnancy information in 2001; weight loss >50kg | Exposure: Milk (glasses/d). No information on fat or sweetener content.; Other exposures: SSB; Comparator: Milk intake (categorical; tertiles equal in number of participants): T1 (lowest intake), T2, T3 (highest); Outcomes and assessment methods:; - Height and weight measured by study personnel. Obesity defined as BMI ≥30; - Baseline, 6y follow-up | [underlined: BMI], Change over time, linear regression:; [underlined: Women (n=923)]:; Not retained in final model; Data NR, P=NS; 24–27y (n=265): Not retained in final model; Data NR, P=NS; 30–39y (n=658): Not retained in final model; Data NR, P=NS; With weight gain >2kg (n=490): Not retained in final model; Data NR, P=NS; [underlined: Men (n=792)]: Not retained in final model; Data NR, p=NS; 24–27y (n=226): Not retained in final model; Data NR, P=NS; 30–39y (n=566): Not retained in final model; Data NR, P=NS; With weight gain >2kg (n=455): Beta=0.126, P=0.0004; [underlined: Incident obesity], OR (95% CI), logistic regression:; Women (n=823): Not retained in final model; Data NR, P=NS; Men (n=689): 2.20 (1.36, 3.56), P=0.001 | Model adjustments:; - TEI: no; - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, diet quality, smoking; - Other: Hormones and inflammatory markers, dietary habits and alcohol use, genetic factors, psychological factors, living habits and environment, childhood factors; Limitations:; - Did not account for key confounders: race and/or ethnicity, diet quality; - Not all key confounders accounted for; Exposure assessment tool not validated; Exposure data only measured at baseline; High attrition (25%) with no information on non-completers; No preregistered data analysis plan;; Funding:; Academy of Finland; Social Insurance Institution of Finland; Kuopio, Tampere and Turku University Hospital Medical Funds; Yrjo Jahnsson Foundation; Juho Vainio Foundation; Paavo Nurmi Foundation; Finnish Foundation of Cardiovascular Research; Finnish Cultural Foundation; Sigrid Juselius Foundation; Tampere Tuberculosis Foundation; Emil Aaltonen Foundation; Signe and Ane Gyllenberg Foundation; Bothnia Welfare Coalition for Research and Knowledge
Kim, 2017 ^65^; PCS, Korean Genome and Epidemiology Study (KoGES), South Korea; Analytic N=4,702; Participant characteristics at baseline: adults, older adults; - Age: Mean ~51y; - Female: 48%; - Race/ethnicity: NR; - SEP: Education: ≤6y ~28%, 7–12y ~57%, >12y ~15%; - Anthropometry: Mean BMI: ~23.8kg/m2; Mean WC: ~80.2 cm; - Physical activity: Mean ~23.5 MET-h/d; - Smoking: ~56% never, ~17% former, ~27% current; - Diet quality: Grains, servings/d, mean (SD): No dairy: 3.2 (1.2); <1: 3.3 (1.4); ≥1 to <4: 3.2 (1.3); ≥4 to ≤7: 3.1 (1.1); >7: 3.1 (1.3); p=0.0421; Vegetables, servings/d, mean (SD): No dairy: 3.2 (2.7); <1: 3.0 (2.3); ≥1 to <4: 3.6 (2.7); ≥4 to ≤7: 3.9 (2.7); >7: 4.6 (4.2); p<0.0001; Fruits, servings/d, mean (SD): No dairy: 1.6 (2.0); <1: 1.8 (2.6); ≥1 to <4: 2.0 (2.7); ≥4 to ≤7: 2.1 (2.6); >7: 2.6 (3.4); p<0.0001; Meat, servings/d, mean (SD): No dairy: 0.5 (0.6); <1: 0.5 (1.1); ≥1 to <4: 0.6 (0.6); ≥4 to ≤7: 0.7(0.6); >7: 0.8 (1.1); p<0.0001; - TEI: Mean ~1971 kcal/d; Study beverage intake at baseline: Milk (svg/wk): 25% none, 21% <1, 30% 1≤ to <4, 20% 4≤ to ≤7, 4% >7; Included: Korean adults aged 40–69y at baseline living in Asan (urban) and Ansung (rural); outcome data at fourth follow-up exam (2009–2010); Excluded: metabolic syndrome at baseline (n=2977), refusal to participate in follow-up exams (n=747), CVD or cancer (n=137), did not complete baseline or follow-up FFQ (n=659) | Exposure: Milk (1 svg=200mL); No information on fat or sweetener content.; Other exposures:; Comparator: Milk intake: categorical; svg/wk (analytic n): None (n=1193);; <1 (n=1004);; ≤1 to <4 (n=1388);; ≤4 to ≤7 (n=926);; >7 (n=191); Outcomes and assessment methods:; - Waist circumference measured in triplicate at the narrowest point between lowest rib and iliac crest. Abdominal obesity defined as waist circumference ≥90cm in men or ≥80 cm in women; - Baseline (2001–2002), 4th Follow-up (2009–2010; Mean~5.6y) | [underlined: Incident abdominal obesity], HR (95% CI), Cox’s proportional hazard; [underlined: Total sample, Unadjusted for TEI]:; None (ref); <1: 0.82 (0.63, 1.06); 1≤ to <4: 0.85 (0.67, 1.07); 4≤ to ≤7: 1.21 (0.94, 1.56); >7: 0.90 (0.55, 1.59); P for trend= 0.4052; [underlined: Total sample, Adjusted for TEI]:; None (ref); <1: 0.83 (0.64, 1.08); 1≤ to <4: 0.86 (0.67, 1.09); 4≤ to ≤7: 1.20 (0.92, 1.58); >7: 0.84 (0.49, 1.44); P for trend= 0.6247; [underlined: Men, Unadjusted for TEI]:; None (ref); <1: 0.70 (0.57, 0.86); 1≤ to <4: 0.79 (0.65, 0.96); 4≤ to ≤7: 0.83 (0.66, 1.04); >7: 0.76 (0.50, 1.16); P for trend= 0.0999; [underlined: Men, Adjusted for TEI]:; None (ref); <1: 0.69 (0.56, 0.85); 1≤ to <4: 0.76 (0.62, 0.93); 4≤ to ≤7: 0.75 (0.58, 0.97); >7: 0.61 (0.38, 1.00); P for trend= 0.0083; [underlined: Women, Unadjusted for TEI]:; None (ref); <1: 0.84 (0.66, 1.06); 1≤ to <4: 0.90 (0.74, 1.10); 4≤ to ≤7: 0.84 (0.68, 1.04); >7: 0.67 (0.44, 1.03); P for trend= 0.0598; [underlined: Women, Adjusted for TEI]:; None (ref); <1: 0.84 (0.66, 1.06); 1≤ to <4: 0.90 (0.73, 1.11); 4≤ to ≤7: 0.82 (0.64, 1.04); >7: 0.64 (0.40, 1.01); P for trend= 0.0717 | Model adjustments:; - TEI: yes and no; - Key confounders: sex, age, socioeconomic position, physical activity, diet quality, smoking; - Other: Alcohol intake, BMI, residential location, energy-adjusted Ca and fibre (only in TEI adjusted analyses); Limitations:; - Did not account for key confounders: race and/or ethnicity, anthropometry at baseline, diet quality; - Not all key confounders accounted for; Start of follow-up and exposure do not coincide; No clear rationale for exposure level category cutoffs (e.g., not quintiles); High attrition (53%) with no information on non-completers; No preregistered data analysis plan; Funding:; Basic Science Research Program of the National Research Foundation of Korea; Ministry of Education, Science, and Technology
Konieczna, 2019 ^66^; PCS, Secondary analysis of PREDIMED trial, Spain; Analytic N=7,009; Participant characteristics at baseline:; Spanish older adults; - Age: Mean (SD): 67y (6.2); - Female: 58%; - Race/ethnicity: All "white, elderly Spanish"; - SEP: Higher education/technician: 7%; - Anthropometry: Body weight, kg, mean (SD): 76.7 (12.0); WC, cm, mean (SD): 100 (10); BMI, kg/m^2, mean (SD): 30.0 (3.8); Obesity prevalence: 47%; Abdominal obesity prevalence: 73%; - Physical activity: METs (min/d), mean (SD): 233 (239); - Smoking: Current smoker: 14%; - Diet quality: Adherence to MedDiet (14-points score), mean (SD): 9 (2); - TEI: Kcal/day, mean (SD): 2239 (543); Study beverage intake at baseline: Baseline (svg/d), mean (SD); Low-fat milk: 1.07 (0.99); Whole-fat milk: 0.23 (0.60); Included: age between 55–80y, free of CVD at enrollment but at risk of CVD based on T2D diagnosis or ≥3 risk factors (hypercholesterolemia, low HDL, overweight/obesity, hypertension, current smoking or family history of premature coronary heart disease); Excluded: missing data on waist circumference, physical activity, or FFQ at baseline (n=291), total energy intake values outside predefined limits (500–3500 kcal/d (women), 800–4000 kcal/d (men)) (n=147) | Exposure: Milk intake, including low-fat milk (skimmed or semi-skimmed milk) and whole-fat milk. Exposure of interest was change in intake expressed in serving/d, calculated as the difference between yearly measured values and values from the previous year.; Other exposures: SSB, LNCSB, 100% juice, coffee and tea; Comparator: Different intake of milk (continuous, svg/d); Outcomes and assessment methods:; - Height and weight: valid measure by study staff; BMI: calculated from height and weight measurements; Waist circumference: determined midway between lowest rib and iliac crest using anthropometric tape; measured in duplicate by trained staff; average of two measurements was analyzed value Absolute change in body weight and WC: calculated as difference between yearly measured values and values from previous year; - Baseline and annually thereafter (mean follow-up 4.8y) | [underlined: ΔWC (cm) over 5y] follow-up by concurrent changes in milk intake (svg/d), β (95% CI), generalized estimating equation; [underlined: Low-fat milk]; Overall: −0.05 (−0.16, 0.06), p=0.393; Men: −0.11 (−0.26, 0.03) p=0.136; Women: −0.01 (−0.16, 0.14), p=0.935; [underlined: Whole-fat milk]; Overall: 0.10 (−0.11, 0.30), p=0.352; Men: −0.04 (−0.29, 0.21), p=0.751; Women: 0.22 (−0.10, 0.54), p=0.178; [underlined: ΔBody weight (kg)] over 5y follow-up by concurrent changes in milk intake (svg/d), β (95% CI), generalized estimating equation; Whole-fat milk: 0.06 (−0.06, 0.17), p=0.367; Low-fat milk: −0.06 (−0.12, 0.00), p=0.038; Sensitivity analysis for low-fat milk:; Adjusted for other food groups significantly associated with anthropometric changes: −0.07 (−0.13, −0.01), P=0.035; Completers only: −0.07 (−0.13, −0.01), P=0.017; Change in energy intake: −0.09 (−0.15, – 0.03), P=0.004; Excluding patients who died: −0.06 (−0.12, 0.00), P=0.062; Excluding 2nd household members: −0.06 (−0.12, 0.00), P=0.066; Excluding participants not individually allocated: −0.06 (−0.13, 0.00), P=0.05; Change in adherence to MedDiet: −0.06 (− 0.13, 0.00), P=0.036 | Model adjustments:; - TEI: Yes (for food groups found to be significantly associated with outcomes); - Key confounders: sex, age, socioeconomic position, anthropometry at baseline, physical activity, smoking, diet quality; - Other: Time (years, due to slight variations in period between successive visits), center, intervention group (combined MedDiets vs. control); for food groups for which the associations with changes in anthropometry were statistically significant, models were additionally adjusted for intake of other foods simultaneously, to estimate mutually adjusted associations. No multi-collinearity was observed between these food groups.; Limitations:; - Did not account for key confounders: race and/or ethnicity; - No preregistered data analysis plan; Limited generalizability; Funding:; CIBER Fisiopatología de la Obesidad y Nutrición (CIBEROBN); Instituto de Salud Carlos III (ISCIII); “FOLIUM” program within the FUTURMed project; Fundación Instituto de Investigación Sanitaria Illes Balears; ERC Advanced Research Grant
Lee, 2020 ^67^; PCS, Ansan-Ansung cohort of the Korean Genome and Epidemiology Study (KoGES), South Korea; Analytic N=8,254; Participant characteristics at baseline: adults; - Age: Mean 52.2 y; Range 40–69; - Female: 46%; - Race/ethnicity: 100% Korean; - SEP: NR; - Anthropometry: BMI ~24.6 kg/m2; 49% overweight; - Physical activity: NR; - Smoking: 29% current smoker; - Diet quality: NR; - TEI: ~2000kcal/d; Study beverage intake at baseline: 79% drink milk <1x/d; Excluded participants with missing data (n=1776) | Exposure: Milk consumption; details NR; Other exposures:; Comparator: Categorical intake (<1x/d vs ≥1x/d); Outcomes and assessment methods:; - Fat-free mass and fat mass were measured using multifrequency bioelectrical impedance analysis (BIA) machines with eight-point tactile electrodes.; Muscle mass was assessed as fat-free mass divided by BMI based on BIA.; - At baseline (2001–2002), and every 2 years over a 14-yr period | [underlined: Muscle mass (Fat-free mass/BMI), change over 14y] by baseline milk intake, between group:; Higher in ≥1x/d group vs <1x/d group, p=0.008; p for interaction=0.061; [underlined: Body fat percentage], change over 14y by baseline milk intake, between group: Lower in ≥1x/d group vs <1x/d group, p=0.010; p for interaction=0.400 | Model adjustments:; - TEI: yes; - Key confounders: sex, age, race and/or ethnicity, smoking; - Other: alcohol drinking; number of chronic diseases; Limitations:; - Did not account for key confounders: socioeconomic position, anthropometry at baseline, physical activity, diet quality; - Exposure not well defined; Exposure data only measured at baseline; No information on non-completers; No preregistered data analysis plan; Funding:; Technology Innovation Program; Ministry of Trade, Industry & Energy (MOTIE, South Korea)
Mozaffarian, 2011 ^68^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-up Study (HPS) , U.S.; Analytic N=NHS = 50,422; NHS II = 47,898; HPS = 22,557; Participant characteristics at baseline:; Adults; - Age: Mean (SD): NHS 52.2y (7.2), NHS II 37.5y (4.1), HPS 50.8y (7.5); - Female: NHS & NHS II: 100% HPS: 0%; - Race/ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: Mean (SD): BMI (kg/m2), NHS 23.7 (1.4), NHS II 23.0 (2.7), HPS 24.7 (1.1); - Physical activity: MET-hr/wk, Mean (SD): NHS 14.8 (9.9), NHS II 21.6 (25.9), HPS 22.9 (15.1); - Smoking: Never smoker: 53%, Past smoker: 33%, Current smoker: 13%, Missing: 1%; - Diet quality: Mean, serv/d Fruit: ~1.5; Vegetables: ~3.5 Whole grains: ~0.6; - TEI: NR; Study beverage intake at baseline: NR; Exclude: obesity, diabetes cancer, or cardiovascular, pulmonary, renal, or liver disease at baseline; missing data on lifestyle habits; implausible energy intake, >9 blank responses on the diet questionnaire; newly pregnant during follow-up; >65y of age | Exposure: Dairy milk: Whole vs. low-fat/skim; Other exposures: 100% juice, SSB, LNCSB; Comparator: Continuous intake (serv/d); Outcomes and assessment methods:; - Weight was collected via self-report from questionnaire; - At baseline, and every 2y over 12- to 20- y follow-up | [underlined: Weight, lb], Linear regression, β (95% CI); [underlined: Whole milk]; Change per svg/d increase: NHS: −0.06 (−0.23, 0.11), P=NS; NHS II: 0.00 (−0.29, 0.30), P=NS; HPS: −0.11 (−0.34, 0.12), P=NS; [underlined: Low-fat/skim milk]; Change per svg/d increase: NHS: 0.04 (−0.02, 0.05), P=NS; NHS II: 0.21 (0.13, 0.29), P<0.001; HPS: −0.05 (−0.14, 0.03), P=NS | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, whole-fat and low-fat dairy, potato chips, potatoes/fries, whole grains, refined grains, sweets and desserts, processed and unprocessed meats, trans fat, fried foods at and away from home, and other beverage types); - Other: Alcohol, television watching, sleep duration; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Not all key confounders accounted for; Self-reported weight; Funding:; NIH; Searle Scholars Program
Pan, 2013 ^69^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-up Study (HPS) , U.S.; Analytic N=NHS = 50,013; NHS II = 52,987; HPS = 21,988; Participant characteristics at baseline:; Adults; - Age: Mean ~47y; - Female: NHS & NHS II: 100% HPS: 0%; - Race/ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: Overweight: 31%, Obesity: 17%, BMI Mean: ~25 kg/m2; - Physical activity: Mean~18 MET-hr/wk; - Smoking: Never smoker: 54%, Past smoker: 33%, Current smoker: 13%; Diet quality: Mean, serv/d SSB: ~0.4; - TEI: NR; Study beverage intake at baseline: Whole milk intake, svg/d, Mean (5th-95th%): NHS; 0.15 (0–1.0), NHS II 0.07 (0–0.43), HPS; 0.13 (0–0.79); Low-fat milk intake, svg/d, Mean (5th-95th%): NHS 0.76 (0–2.5), NHS II 0.94 (0–2.5), HPS 0.73 (0–2.5); Exclude: missing weight, beverage, or lifestyle habits data; inadequate diet data; implausible TEI; >65y of age; diabetes, cancer, cardiovascular, pulmonary, renal or liver disease; pregnancy during follow up | Exposure: Dairy milk: Whole vs. low-fat/skim; Other exposures: 100% juice, SSB, LNCSB, Coffee/Tea; Comparator: Continuous intake (serv/d); Outcomes and assessment methods:; - Weight was collected via self-report from questionnaire; - At baseline, and every 2y over 16- to 20- y follow-up | [underlined: Weight change over each 4y] period, kg, Linear regression, β (95% CI); [underlined: Whole milk]; Change per svg/d increase:; NHS: 0.05 (−0.06, 0.16), P=NR; NHS II: −0.14 (−0.38, 0.10), P=NR; HPS: 0.03 (−0.11, 0.18), P=NR; Stratified by age: ≤50y, >50y; NHS: 0.12 (−0.07, 0.31), 0.09 (−0.05, 0.23), P=0.53; NHS II: −0.09 (−0.34, 0.16), −0.63 (−1.37, 0.11), P=0.68; HPS: 0.10 (−0.12, 0.33), −0.01 (−0.20, 0.18), P=0.11; Stratified by BMI (kg/m2): <25, 25–29.9, ≥30; NHS: 0.02 (−0.09, 0.12), 0.20 (−0.01, 0.42), 0.05 (−0.38, 0.49), P=0.003; NHS II: −0.16 (−0.38, 0.06), 0.20 (−0.30, 0.71), −0.42 (−1.20, 0.37), P=0.36; HPS: −0.14 (−0.30, 0.02), 0.14 (−0.07, 0.35), 0.73 (−0.08, 1.54), P<0.001; [underlined: Low-fat milk]; Change per svg/d increase:; NHS: 0.02 (−0.02, 0.05), P=NR; NHS II: 0.09 (0.05, −0.13), P=NR; HPS: −0.03 (−0.08, 0.01), P=NR; Stratified by age: ≤50y, >50y:; NHS: −0.01 (−0.09, 0.06), 0.16 (0.12, 0.20), P=0.07; NHS II: 0.09 (0.05, 0.13), 0.10 (−0.01, 0.20), P=0.93; HPS: −0.08 (−0.16, −0.01), −0.01 (−0.07, 0.04), P=0.048; Stratified by BMI (kg/m2): <25, 25–29.9, ≥30; NHS: 0.01 (−0.02, 0.04), −0.02 (−0.08, 0.04), 0.01 (−0.10, 0.13), P=0.30; NHS II: 0.07 (0.03, 0.11), 0.10 (0.02, 0.17), 0.14 (0.01, 0.26), P=0.22; HPS: 0.05 (0.00, 0.09), −0.07 (−0.14, −0.01), −0.12 (−0.35, 0.11), P=0.002 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (fruits, vegetables, whole grain, refined grain, potatoes, potato chips, red meat, other dairy products, sweets and deserts, nuts, fried foods, and trans fat, and other beverage types); - Other: Alcohol, protein, television watching; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Not all key confounders accounted for; Self-reported weight; Funding:; NIH
Pereira, 2002 ^70^; PCS, Coronary Artery Risk Development in Young Adults (CARDIA), U.S.; Analytic N=3,157; Participant characteristics at baseline:; Adults; - Age: Mean: ~25y; - Female: 56%; - Race/ethnicity: Black: 45%; White: 55%; - SEP: Education Mean, ~15y; - Anthropometry: BMI kg/m2: 71%: <25 , 29%: ≥25; - Physical activity: Units/d of total activitiy, Mean: ~377; - Smoking: Current: 25%; - Diet quality: Mean, times/wk Soda: ~4.5; Fruit + Vegetables: ~22; - TEI: NR; Study beverage intake at baseline: Milk and milk drink intake (times/wk): Blacks, Median~5.0; Whites, Median~8.1; Exclude: missing dietary data, ununsually high or low dietary intake, pregancy at baseline or within 180 days of year 10 exam, medications that affect blood lipids, | Exposure: Dairy milk: total milk and milk drinks (not further defined); Other exposures: None; Comparator: Continuous intake (times/d); Outcomes and assessment methods:; - Height measured to nearest 0.5 cm with vertical ruler; - Weight measured to nearest 0.2 kg with calibrated balance beam scale; - BMI computed as weight in kg divided by height in meters squared; - Waist and hips measured to nearest 0.5 cm with tape in duplicate; - Waist-hip ratio (WHR) computed from average of 2 values for each measure; - Obesity (BMI≥30, or WHR≥0.85 for women and ≥0.90 for men); - At baseline, 7y follow-up | [underlined: Obesity (BMI≥30, or WHR≥0.85 for women and ≥0.90 for men)], Logistic regression; Per 1 daily eating occasion average among individuals who were overweight at baseline; OR: 0.83, 95% CI: 0.68, 1.00 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, race/ethnicity, SES, anthropometry at baseline, physical activity, smoking, diet quality (energy density, fiber, whole and refined grains, meat, fruit, vegetables, soda); - Other: Protein, alcohol, medications, supplements, dietary intake of micronutrients (magnesium, calcium, potassium, and vitamin D); Limitations:; - Did not account for key confounders:; - Baseline and analytic n not clear, analysis based on eating occasion rather than amount of milk intake, no information on non-completers, so preregistered data analysis plan; Funding:; Children’s Hospital League; Charles H. Hood Foundation; NIDDK; General Mills, Inc; NHLBI
Rautiainen, 2016 ^71^; PCS, Women’s Health Study (prospective analyses from an RCT), U.S.; Analytic N=18,438; Participant characteristics at baseline:; Adult women: Middle-aged and older; - Age: Mean: ~54.5y; - Female: 100%; - Race/ethnicity: Predominantly Caucasian; - SEP: Predominantly health professionals; - Anthropometry: BMI, Mean~22.4 kg/m2; - Physical activity: Metabolic equivalent task hours per week, Mean~17.0; - Smoking: Current: 14%; - Diet quality: Fruit + Vegetable, Mean serv/d: ~6 (increased significantly with each quintile increase in dairy intake); - TEI: Mean: ~1,730kcal/d; Study beverage intake at baseline: Skim milk intake (svg/d): Mean~0.8; frequency: 0: 17.1%, >0 to <0.5: 34.2%, 0.5 to <1: 8.5%, ≥1: 40.2%; Whole milk intake (svg/d): Mean~0.04; frequency: 0: 87.8%, >0 to <0.5: 10.1%, 0.5 to <1: 0.4%, ≥1: 1.7%; Exclude: men, women aged <45y, BMI <18.5 or >25kg/m2, intending to become pregnant, history of MI, stroke, transient ischemic attack, cancer, diabetes, missing data on dairy intake, insufficient amount of dietary data, TEI outside 600–3500kcal/d | Exposure: Dairy milk: Skim milk, whole milk; Other exposures: None; Comparator: Categorical intake: 0 (ref), >0 to <0.5, 0.5 to <1, ≥1 serv/d; Outcomes and assessment methods:; - Height and weight were self-reported; - BMI calculated as weight in kg divided by height in meters squared; - Weight categories: normal weight (BMI 18.5 to <25), overweight (BMI 25 to <30), obesity (BMI≥30); - Risk of becoming overweight or obesity: from baseline to date of questionnaire on which they first reported overweight or obesity, their date of death, or end of follow-up, whichever occurred first; - At baseline, and 2, 3, 5, 6, 9, 11y follow ups and annually thereafter until 17y follow up | [underlined: Overweight or Obesity at 17y follow up]; [underlined: (BMI ≥25)], HR (95% CI), Cox proportional hazard; [underlined: Skim Milk (svg/d)] 0 (Ref, n=3127); >0 to <0.5 (n=6248): 1.07 (1.00, 1.14); 0.5 to <1 (n=1545): 1.03 (0.94, 1.13); ≥1 (n=7344): 1.05 (0.98, 1.12); P for trend: 0.44; [underlined: Whole Milk (svg/d)] 0 (Ref, n=15,703); >0 to <0.5 (n=1808): 0.95 (0.89, 1.03); 0.5 to <1 (n=74): 0.96 (0.68, 1.34); ≥1 (n=304): 0.88 (0.73, 1.05); P for trend: 0.14 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (F&V intake); - Other: Supplements, alcohol, randomization treatment, postmenopausal status, hormone replacement therapy, history of hypercholesterolemia, history of hypertension; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Not all key confounders accounted for; exposure measured at baseline only; height and weight were self-reported no information on non-completers; no preregistered data analysis plan; racial/ethnic minorities under-represented in study sample; Funding:; NIH
Romaguera, 2011 ^72^; PCS, European Prospective Investigation into Cancer and Nutrition (EPIC) study, DiOGenes (Diet, Obesity, and Genes) project, Italy, UK, the Netherlands, Germany, Denmark; Analytic N=48,631; Participant characteristics at baseline:; Adults; - Age: 20–60y; - Female: 60%; - Race/ethnicity: NR; - SEP: NR; - Anthropometry: NR; - Physical activity: NR; - Smoking: NR; - Diet quality: Mean (SD), g/d Fruits: ~180; Vegetables: ~170 Soft drinks: ~900; - TEI: NR; Study beverage intake at baseline: Milk intake, g/d, Mean (SD): Men, 238.44 (263.06), Range=80.20–364.15; Women, 200.45 (221.19), Range=81.30–332.93; Exclude: no blood sample data, pregnancy, missing diet or anthropometric data, highest and lowest 1% of TEI:energy requirement ratio, chronic disease (cancer, CVD, diabetes) at baseline or follow up, unrelistic anthropometric measurements, baseline age >60y or follow-up age >65y, missing data on smoking or change in smoking status from baseline to follow up | Exposure: Milk: no further definition given; Other exposures: 100% juice, SSB, Coffee/Tea; Comparator: Continuous, 100 kcal/d; Outcomes and assessment methods:; - Weight and height measured using standard protocol or via self-report; - Waist circumference (WC) measured either midway between the lowest rib and iliac crest, at the narrowest torso circumference, or via self-report; - BMI calculated as weight (kg) divided by height (m) squared; - Waist circumference for a given body mass index (WCBMI) calculated as the residual values from gender- and centre-specific regression equations of WC on BMI using baseline and follow-up values of WC and BMI; - Baseline, 5.5y follow up | [underlined: ∆WCBMI] (Waist circumference for a given body mass index), cm/y; Association between milk intake and annual change in WC for given BMI; β2 (95% CI), Linear regression; All: −0.01 (−0.02, −0.00), P=0.005; Men: −0.01 (−0.02, −0.00), P=0.013; Women: −0.02 (−0.03, −0.01), P=0.005; Interaction by gender: P=NS | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race/ethnicity, SES, anthropometry at baseline, physical activity, smoking; - Other: Alcohol, follow-up duration, menopausal status and hormone replacement therapy use (in women); Limitations:; - Did not account for key confounders: Diet quality; - Exposure measured at baseline only; excluded participants with chronic disease at follow up; Funding:; European Union; Danish Strategic Research Council
Rosell, 2006 ^73^; PCS, Swedish Mammography Cohort, Sweden; Analytic N=19,352; Participant characteristics at baseline: Adults: Perimenopausal or early postmenopausal women; - Age: Mean (SD): 46.3 (4.5)y, Range=40–55y; - Female: 100%; - Race/ethnicity: NR; - SEP: Education: <10y: 63%, 10–12y: 10%, >12y: 27%; - Anthropometry: BMI Mean (SD): 23.7 (3.5) kg/m2; - Physical activity: NR; - Smoking: NR; - Diet quality: NR; - TEI: Mean: ~1,600kca/d; Study beverage intake at baseline:; - Whole milk and sour milk, 3% fat (svg/d): <1 69.2%, ≥1 30.8%; - Medium-fat milk, 1.5% fat (svg/d): <1 83.2%, ≥1 16.8%; - Low-fat milk and sour milk, 0.5% fat (svg/d): <1 63.9%, ≥1 36.1%; Exclude: outside the 40–55y age range; missing weight or height data; history of cancer, CVD, or diabetes; mean BMI change from baseline to follow up >2/y | Exposure: Milk intake: whole milk (3% fat), medium-fat milk (1.5%), low-fat milk (≤0.5% fat), whole sour milk (3% fat), low-fat sour milk (0.5%); Other exposures: None; Comparator: Categorical change at 9y follow up, serv/d; - No change, Constant intake of <1 (ref); - Increase from <1 to ≥1; - No change, Constant intake ≥1; - Decrease from ≥1 to <1 ); Outcomes and assessment methods:; - Body weight was self-reported to the nearest 0.1 kg; - Mean weight gain ≥1 kg/y calculated as change in weight from baseline to follow-up divided by number of years of follow-up (participants categorized into 2 groups according to mean annual weight change: <1 or ≥1 kg/y); - Baseline, 9y follow up | Whole milk and sour milk, 3% fat; [underlined: Weight Gain ≥1 kg/yr] by change in whole milk/sour milk intake (svg/d): OR (95% CI), Logistic regression; No change, <1 (Ref); Increase <1 to ≥1: 0.94 (0.82, 1.07); No change, ≥1: 0.85 (0.73, 0.99); Decrease ≥1 to <1: 0.91 (0.79, 1.05); [underlined: Whole milk and sour milk*BMI (<25, ≥25)]: p=0.003 (Constant intake ≥1 svg/d lower risk of gaining ≥1kg/y in normal wt women only; Data NR); [underlined: Weight gain]: Linear regression, β; [underlined: BMI<25]; No change, <1(Ref); Increase <1 to ≥1: −0.40, P=0.004 No change, ≥1: −0.42, P=0.004 Decrease ≥1 to <1: −0.34, P=0.014; [underlined: BMI>25]: P=NS (Data NR); Medium-fat milk, 1.5% fat; [underlined: Weight Gain ≥1 kg/yr] by change in medium-fat milk intake (svg/d): OR (95% CI), Logistic regression; No change, <1 (Ref); Increase <1 to ≥1: 0.95 (0.82, 1.10); No change, ≥1: 0.90 (0.74, 1.10); Decrease ≥1 to <1: 0.84 (0.72, 0.99); Medium fat milk* BMI: P=0.016; Low-fat milk and sour milk, 0.5% fat; [underlined: Weight Gain ≥1 kg/yr] by change in low-fat milk/sour milk intake (svg/d): OR (95% CI), Logistic regression; No change, <1 (Ref); Increase <1 to ≥1: 1.09 (0.95, 1.24); No change, ≥1: 1.03 (0.90, 1.18); Decrease ≥1 to <1: 1.01 (0.87, 1.18); Low-fat milk*BMI: P=0.039 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, SES, anthropometry at baseline, physical activity, smoking, diet quality; - Other: Sugar, protein, fiber, supplements, alcohol, parity, calcium intake, conjugated linoleic acid intake; Limitations:; - Did not account for key confounders: Race and/or ethnicity, physical activity; - Not all key confounders accounted for; weight was self-reported; no information on non-completers; no preregistered data analysis plan; Funding:; Swedish Research Council/Longitudinal Studies; The Swedish Cancer Foundation; The Foundation of the Karolinska Institutet
Shin, 2013^74^; PCS, Anseong and Ansan cohort of the Korean Genome and Epidemiology Study, South Korea; Analytic N=7,240; Participant characteristics at baseline:; Adults: Middle-aged; - Age: Mean: 52y Range: 40–69y; - Female: 50%; - Race/ethnicity: NR; - SEP: Education level:; Elementary school graduate: 29%, Middle school graduate 24%, High school graduate 34%, College graduate or higher 14%;; Income level (KRW/mo): <1 million: 31.6%, 1–1.99 million: 30.6%, 2–2.99 million: 19.2%, >3 million: 18.6%; - Anthropometry: BMI, Mean~24.8; Abdominal obesity: 25.2%; - Physical activity: METs/d Mean: ~1530; - Smoking: Pack/yr, Mean: !6.1; - Diet quality: NR; - TEI: NR; Study beverage intake at baseline: Milk intake (times/wk):; - None: 36.7%,; - 1: 13.6%,; - 2–3: 14.8%,; - 4–6: 12.9%,; - ≥7: 22.0%; Exclude: MetS, incomplete nutritional survey | Exposure: Milk: "Most of the dairy product consumed was whole milk because low-fat milk is not popular"; Other exposures: None; Comparator: Categorical intake, times/wk:; - None; - 1; - 2–3; - 4–6; - ≥7; Outcomes and assessment methods:; - Waist circumference measured in triplicate by trained health professional; - Abdominal obesity defined as waist circumference ≥90 cm for men and ≥85 cm for women; - At baseline, 45.5mo follow-up (IQR 44.4–47.1mo) | [underlined: Abdominal Obesity], HR (95% CI), Cox proportional hazard; None (Ref, n=2243); 1 time/wk (n=831): 1.01 (0.83, 1.22); 2–3 times/wk (n=953): 1.03 (0.85, 1.25); 4–6 times/wk (n=816): 0.88 (0.71, 1.09); ≥7 times/wk (n=1379): 0.82 (0.68, 0.97); P for trend: 0.019 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, SES, anthropometry at baseline, physical activity, smoking; - Other: Alcohol; Limitations:; - Did not account for key confounders: Race and/or ethnicity, diet quality; - Not all key confounders accounted for; no preregistered data analysis plan; Funding:; Korea Health Industry Development Institute
Smith, 2015 ^75^; PCS, Nurses Health Study (NHS) + NHS II + Health Professionals Follow-Up Study (HPS), U.S.; Analytic N=NHS = 46,994; NHS II = 47,928; HPS = 25,862; Participant characteristics at baseline:; Adults; - Age: Mean (SD):; NHS 48.9 (2.7)y, NHS II 37.7 (3.2)y, HPS 47.3 (2.7)y; - Female: NHS & NHS II: 100% HPS: 0%; - Race/ethnicity: Primarily white; - SEP: Primarily well-educated; - Anthropometry: BMI Mean (SD), kg/m2 NHS 23.7 (1.4), NHS II 23.0 (2.4), HPS 24.8 (1.1); - Physical activity: METs/wk, Mean (SD): NHS 14.9 (9.9), NHS II 21.7 (23.1), HPS 20.7 (13.8); - Smoking: NR; - Diet quality: NR; - TEI: Mean kcal/d; NHS: 1805 (244),; NHS II: 1779 (423),; HPS: 1980 (279); Study beverage intake at baseline: • Whole milk intake, svg/d, Mean (SD): NHS 0.15 (0.21), NHS II 0.07 (0.24), HPS 0.14 (0.22); - Low-fat milk intake (skim, 1%, & 2%), svg/d, Mean (SD): NHS 0.74 (0.43), NHS II 0.94 (0.79), HPS 0.73 (0.48); Exclude: obesity, age >65y, missing diet or weight data, implausibleTEI, chronic disease (cancer, cardiovascular disease, diabetes, renal disease, pulmonary disease, rheumatologic disorders, or ulcerative colitis), pregnancy | Exposure: Dairy milk: Whole milk, Low-fat milk (skim, 1%, 2%); Other exposures: None; Comparator: Continuous, serv/d; Outcomes and assessment methods:; - Weight was collected via self-report from questionnaire; weight change was calculated every 4y; - At baseline, and every 2y over 16- to 24- y follow-up | Whole milk; [underlined: Weight, kg], Linear regression, β (95% CI) 4-year change per svg/d increase of whole milk:; [underlined: Adjusted for glycemic load]; NHS: −0.08 (−0.19, 0.03), P=0.16; NHS II: −0.09 (−0.28, 0.10), P=0.36; HPS: 0.08 (−0.07, 0.22), P=0.30; [underlined: Adjusted for glycemic index]; NHS: 0.01 (−0.10, 0.12), P=0.80; NHS II: 0.05 (−0.14, 0.24), P=0.58; HPS: 0.15 (0.00, 0.29), P=0.05; Low-fat milk (skim, 1% and 2%); [underlined: Weight, kg], Linear regression, β (95% CI) 4-year change per svg/d increase of low-fat milk:; [underlined: Adjusted for glycemic load]; NHS: −0.01 (−0.04, 0.02), P=0.57; NHS II: −0.03 (−0.06, 0.00), P=0.06; HPS: 0.04 (0.00, 0.09), P=0.09; [underlined: Adjusted for glycemic index]; NHS: 0.08 (0.05, 0.11), P<0.0001; NHS II: 0.07 (0.03, 0.10), P<0.0001; HPS: 0.11 (0.06, 0.16), P<0.0001 | Model adjustments:; - TEI: no; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (F&V intake); - Other: Sugar, protein, alcohol, glycemic load, glycemic index, sleep duration, television watching, fried foods consumed at home and away from home, trans fats; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Not all key confounders accounted for; self-reported outcome data; Funding:; Canadian Institutes of Health Research; NHLBI; NIH
Snijder, 2008 ^76^; PCS, Hoorn Study, The Netherlands; Analytic N=1,124; Participant characteristics at baseline:; Adults: Middle-aged and older; - Age: Mean: ~60y Range: 50–75y; - Female: 54%; - Race/ethnicity: White: 100%; - SEP: NR; - Anthropometry: BMI Mean: 26 kg/m2; - Physical activity: Habitual, Mean: ~4.3 hr/d; Sports, yes: ~33%; - Smoking: Yes: ~30%; - Diet quality: NR; - TEI: Mean: ~2,090 kcal/d; Study beverage intake at baseline: NR; Exclude: outside age range of 50–75y, missing data | Exposure: Dairy milk: Skim, low-fat, and whole combined; Other exposures: None; Comparator: Continuous intake (serv/d); Outcomes and assessment methods:; - Weight, height, waist, and hip circumference measured via physical examination; - BMI calculated as weight in kilograms divided by height in meters squared; - Waist-to-hip ratio calculated as waist circumference divided by hip circumference; - Baseline, 6.4y follow up | [underlined: Waist Circumference,] Linear regression P=NS, Data NR; [underlined: Waist-to-Hip Ratio], Linear regression P=NS, Data NR; [underlined: Weight], Linear regression P=NS, Data NR; [underlined: BMI], Linear regression P=NS, Data NR | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, race/ethnicity, SES, anthropometry at baseline, physical activity, smoking; - Other: Fiber, medications, alcohol; Limitations:; - Did not account for key confounders: Diet quality; - Selection bias: participants included in the analyses had lower BMI, WC, and W:H compared to those not included; no diff in dairy consumption; exposure measured at baseline only; no preregistered data analysis plan; Funding:; Vrije Universiteit Amsterdam; VU University Medical Center; Dutch Diabetes Research Foundation; Dutch Organization for Scientific Research; Netherlands Heart Foundation; Health Research and Development Council of Netherlands; Dutch Dairy Association
Trichia, 2020 ^77^; PCS, EPIC-Norfolk, England; Analytic N=15,612; Participant characteristics at baseline:; Adults; - Age: 58.6 (SD=8.9); - Female: 56%; - Race/ethnicity: NR; - SEP: Occupation:; Low (technical / semi-routine, routine): 36.6%; Medium (lower managerial / intermediate): 16.7%; High (professional / higher managerial): 46.7%; Education: Low: 43.4%; Medium: 41.9%; High: 14.7%; Marital status: Married: 82.6%; - Anthropometry: Mean (SD) Weight (kg): 73.0 (12.8); BMI: 26.1 (3.7); Waist circumference (cm): 87.3 (12.1); Waist-to-hip ratio: 0.8 (0.1); - Physical activity: Moderately inactive 29.6% ; Moderately active 24.3% , Active 19.3%; - Smoking: Former 41.4%; Current 9.4%; - Diet quality: Mean intake (g/day): 250 g fruit, 241g vegetables, 33g SSB, 128 g alochol beverges, 79 g whole grain cereals, 62 grams red meat, 37 grams fish; - TEI: 2018 (552); Study beverage intake at baseline: Milk intake at baseline (servings/d), Mean (SD); Total: 1.73 (0.82); Full-fat: 0.33 (0.78); Low-fat: 1.39 (1.00); Excluded: terminal or malignant disease, inability to attend local clinic, alcoholism, psychiatric disorder, inadequate command of English, blindness, missing dietary data (673), no follow up (8507), extreme values of dietary intakes TEI of <800 and >4000 kcal/day for men and <500 and >3500 for women (847), extreme changes in dairy consumption or cardiometabolic markers (≥3 SD) | Exposure: Full-fat milk: Goat’s milk; Channel Islands milk; silver top full-cream milk; evaporated milk, whole diluted; sheep’s milk; Low-fat milk: Semi-skimmed milk, skimmed milk, skimmed milk as reconstituted dried milk; Total milk: full-fat milk + low-fat milk 1 serving = 200g; Other exposures:; Comparator: change in intake between baseline and follow up; low vs high fat milk; Outcomes and assessment methods:; - BMI, WC, change in weight, waist to hip ratio (all measured in health clinic); - Baseline, first follow up (Mean: 3.7y); second follow up (Mean: 12.6y) | [underlined: Waist circumference change, baseline to 3.7y follow up (cm)] by change in milk intake, baseline to ~3.7y follow up (serv/d), β (95% CI), Linear regression (n=14,227); Total milk: −0.07 (−0.19, 0.06); Full-fat milk: 0.04 (−0.19, 0.28); Low-fat milk: −0.04 (−0.17, 0.08); [underlined: Waist circumference 3.7y & 12.6y follow ups (cm)] by milk intake baseline & 3.7y follow up, (serv/d), β (95% CI), Linear mixed model (n=14,199); Total milk: 0.01 (−0.13, 0.15); Full-fat milk: −0.28 (−0.48, −0.08); Low-fat milk: 0.01 (−0.13, 0.15); [underlined: Waist-to-hip ratio change, baseline to]; [underlined: 3.7y follow up] by change in milk intake, baseline to ~3.7y follow up (serv/d), β (95% CI), Linear regression (n=14,213); Total milk: −0.001 (−0.002, 0.001); Full-fat milk: −0.001 (−0.003, 0.002); Low-fat milk: −0.001 (−0.002, 0.001); [underlined: Waist-to-hip ratio 3.7y & 12.6y follow ups] by milk intake baseline & 3.7y follow up, (serv/d), β (95% CI), Linear mixed model (n=14,218); Total milk: −0.001 (−0.002, 0.00); Full-fat milk: −0.004 (−0.006, −0.002); Low-fat milk: −0.001 (−0.002, 0.00); [underlined: Body fat percentage 3.7y & 12.6y follow ups] by milk intake baseline & 3.7y follow up (serv/d), β (95% CI), Linear mixed model (n=14,019); Total milk: 0.10 (−0.02, 0.21); Full-fat milk: −0.04 (−0.18, 0.11); Low-fat milk: 0.12 (0.02, 0.23); Associations stratified by age (<50y, 50–60y, ≥60y), sex, and weight status (normal, ovwt/ob) were all non-significant (data not shown); [underlined: Weight change, baseline to ~3.7y follow up (kg)] by change in milk intake, baseline to ~3.7y follow up (serv/d), β (95% CI), Linear regression (n=14,044); Total milk: 0.05 (−0.06, 0.17); Full-fat milk: 0.23 (0.02, 0.45); Low-fat milk: 0.05 (−0.06, 0.16); [underlined: Weight ~3.7y & 12.6y follow ups (kg)] by milk intake baseline & 3.7y follow up, (serv/d), β (95% CI), Linear mixed model (n=14,145); Total milk: 0.16 (0.07, 0.26); Full-fat milk: 0.09 (−0.04, 0.22); Low-fat milk: 0.16 (0.07, 0.25); [underlined: BMI change, baseline to ~3.7y follow up (kg/m^2^)] by change in milk intake, baseline to ~3.7y follow up (serv/d), β (95% CI), Linear regression (n=14,134); Total milk: 0.02 (−0.02, 0.06); Full-fat milk: 0.09 (0.01, 0.17); Low-fat milk: 0.02 (−0.02, 0.06); BMI ~3.7y & 12.6y follow ups (kg/m^2^) by milk intake baseline & 3.7y follow up, (serv/d), β (95% CI), Linear mixed model (n=14,107); Total milk: 0.12 (0.06, 0.19); Full-fat milk: −0.01 (−0.09, 0.07); Low-fat milk: 0.13 (0.08, 0.19); Associations stratified by age (<50y, 50–60y, ≥60y), sex, and weight status (normal, ovwt/ob) were all non-significant (data not shown) | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, socioeconomic position, anthropometry at baseline (outcomes of waist circumference & waist-to-hip ratio), physical activity, smoking, diet quality ( intake of fruit, vegetables, potatoes, legumes, nuts, processed cereals, whole-grain cereals, poultry and eggs, red meat, processed meat, fish, sauces, margarine, sweet snacks, sugar-sweetened beverages, artificially sweetened beverages, fruit juice, coffee, tea, alcohol, dietary supplements); - Other: Medications (lipid-lowering or anti-hypertensive), hormone replacement therapy, follow up duration; Limitations:; - Did not account for key confounders: Race and/or ethnicity; anthropometry at baseline (outcomes of weight and BMI); - Not all key confounders accounted for; Start of follow-up and exposure do not coincide; No information on non-completers; No preregistered data analysis plan; Funding:; Medical Research Council, Cancer Research UK, Medical Research Council Epidemiology Unit core funding
Vergnaud, 2008 ^78^; PCS, Prospective analyses of Supplementation en Vitamines et Mineraux Antioxidants Study (RCT), France; Analytic N=2,267; Participant characteristics at baseline:; Adults; - Age: Men, 51.5 (4.4)y; Women, 50.8 (4.3)y; - Female: 45%; - Race/ethnicity: NR; - SEP: Education level, Primary 24.0%, Secondary 38.8%, University or equivalent 37.2%; - Anthropometry: Mean (SD): Men: BMI, 25.2 (3.0) kg/m2; Waist, 90.3 (9.0) cm;; Women: BMI, 23.5 (3.7); Waist, 76.1 (9.4) cm; - Physical activity: Irregular 23.9%, Low 27.4%, Equivalent to ≥1 hr walking/d 48.7%; - Smoking: Never smoker 49.5%, Previous smoker 40.0%, Current smoker 10.5%; - Diet quality: NR; - TEI: Mean (SD) kcal/d; Men: 2310 (541); Women: 1759 (446); Study beverage intake at baseline: Milk intake, svg/d, Mean (SD): Men, 0.71 (0.84); Women, 0.65 (0.76) | Exposure: Milk: no further definition given Other exposures: None; Comparator: Categorical intake (quartiles); Outcomes and assessment methods:; - Weight measured on electric scale using standardized procedures; change calculated in absolute terms as difference between last and first measure; - Waist circumference (midway between lower ribs and iliac crest) measured using standardized procedures; change calculated in absolute terms as difference between last and first measure; - Baseline, 6y follow up | [underlined: Waist Circumference change over 6y], Mean (SE), ANCOVA; [underlined: Men, Normal weight at baseline, n=621]; Quartile 1 (svg/d): 0.85 (0.38); Quartile 2: 1.92 (0.44); Quartile 3: 1.08 (0.43); Quartile 4: 1.25 (0.40), P trend: 0.97; [underlined: Men, Overweight at baseline, n=624]; Quartile 1 (svg/d): 1.85 (0.39); Quartile 2: 0.69 (0.42); Quartile 3: 1.36 (0.43); Quartile 4: −0.08 (0.48), P trend: 0.02; [underlined: Women, Normal weight at baseline, n=763]; Quartile 1 (svg/d): 2.56 (0.42); Quartile 2: 2.17 (0.45); Quartile 3: 2.16 (0.45); Quartile 4: 2.17 (0.46), P trend: 0.59; [underlined: Women, Overweight at baseline, n=259]; Quartile 1 (svg/d): 0.26 (0.83); Quartile 2: 3.20 (0.91); Quartile 3: 1.02 (0.87); Quartile 4: 3.93 (0.97), P trend: 0.08; [underlined: Weight change over 6y], Mean (SE), ANCOVA; [underlined: Men, Normal weight at baseline, n=621]; Quartile 1 (svg/d): 1.87 (0.26); Quartile 2: 2.01 (0.31); Quartile 3: 2.03 (0.30); Quartile 4: 2.06 (0.28), P for trend: 0.67; [underlined: Men, Overweight at baseline, n=624]; Quartile 1 (svg/d): 2.47 (0.32); Quartile 2: 1.86 (0.34); Quartile 3: 2.22 (0.35); Quartile 4: 0.98 (0.40), P for trend: 0.02; [underlined: Women, Normal weight at baseline, n=763]; Quartile 1 (svg/d): 1.65 (0.25); Quartile 2: 1.69 (0.26); Quartile 3: 1.69 (0.26); Quartile 4: 2.11 (0.27), P for trend: 0.27; [underlined: Women, Overweight at baseline, n=259]; Quartile 1 (svg/d): 0.37 (0.66); Quartile 2: 2.76 (0.72); Quartile 3: 1.83 (0.70); Quartile 4: 2.45 (0.78), P for trend: 0.18 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, SES, anthropometry at baseline, physical activity, smoking, diet quality (mean adequacy ratio index (MARi)); - Other: Supplements, alcohol, intervention group, menopausal status (for women), consumption of cheese and yogurt; Limitations:; - Did not account for key confounders: Race and/or ethnicity; - Not all key confounders accounted for; selection bias: participants excluded if they did not complete six 24-hr diet records in first 18mo; no preregistered analysis plan; Funding:; French National Health Ministry
Wang, 2014 ^79^; PCS, Framingham Heart Study Offspring Cohort, U.S; Analytic N=3,440; Participant characteristics at baseline:; Adults; - Age: Mean (SD): 54.5 (9.6), Range=26–84y; - Female: 54%; - Race/ethnicity: Mostly Caucasian American of European descent; - SEP: NR; - Anthropometry: Mean (SD): BMI (kg/m2): 27.4 (4.9); Weight (kg): 77.5 (16.6); Waist circumference (cm): 92.5 (14.2); - Physical activity: Mean (SD): Index in metabolic equivalents, 34.9(6.3); - Smoking: Current, regular: 19%; - Diet quality: Mean, serv/wk Fruits & Vegetables: 28 Whole grain: 9; - TEI: Mean (SD) kcal/d: 1,875 (622); Study beverage intake at baseline: • Skim/low fat milk (svg/wk): Mean=4.83, SD=6.01; - Frequency of skim/low fat milk (svg/wk): <1: 29.2%; 1≤3: 15.1%; ≥3: 55.7%; Exclude: missing/invalid FFQ data, attending <2/4 examinations | Exposure: Milk intake: Skim/low-fat (collected data for whole milk but did not report results); Other exposures: None; Comparator: Categorical intake; - <1; - 1-<3; - ≥3 serv/wk; Outcomes and assessment methods:; - Height and weight measured at a standardized physical examination; - Waist circumference measured at level of umbilicus underneath gown by a trained professional; - Baseline, 13y follow up | [underlined: Waist circumference]: annualized change over 13y, mean (SE), Repeated-measure regression; - <1 svg/wk (n=2403): 0.67 (0.03); - 1-<3 svg/wk (n=1248): 0.69 (0.04); - ≥3 svg/wk (n=4592): 0.69 (0.03); P for trend: 0.53; [underlined: Weight]: annualized weight change over 13y, mean (SE), Repeated-measure regression; - <1 svg/wk (n=2403): 0.13 (0.03); - 1-<3 svg/wk (n=1248): 0.15 (0.04); - ≥3 svg/wk (n=4592): 0.16 (0.02); P for trend: 0.33 | Model adjustments:; - TEI: yes; - Key confounders: Sex, age, anthropometry at baseline, physical activity, smoking, diet quality (Dietary Guidelines Adherence Index); - Other: Medications, individual food groups, diabetic status, systolic blood pressure, blood lipid profile; Limitations:; - Did not account for key confounders: Race and/or ethnicity, SEP; - Not all key confounders accounted for; missing data: Participants who were excluded were older and less healthy; no preregistered data analysis plan; racial/ethnic minorities were under-represented in the study sample; Funding:; NHLBI; USDA; The Dannon Company, Inc.; General Mills Bell Institute of Health and Nutrition

a BMI: body mass index; CI: confidence interval; CDC: Centers for Disease Control; d: day(s); EPIC: European Prospective Investigations into Cancer and Nutrition Study; FFQ: food frequency questionnaire; g: gram(s); HAZ: height-for-age z-score; hr: hour; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); L: liter; LNCSB: low- and no-calorie sweetened beverage(s); m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NHS: Nurses’ Health Study; NIH: National Institutes of Health; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; REF: reference group; RCT: Randomized controlled trial; SD: standard deviation; SE: standard error; SEP: Socioeconomic position; SSB: sugar-sweetened beverage(s); svg: serving(s); TEI: total energy intake; USDA: United States Department of Agriculture; WHZ: weight-for-height z-score; wk: week(s); y: year(s)

Table 20 Risk of bias for randomized controlled trials examining dairy milk and milk alternative consumption in adults and body composition and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) or (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Barr, 2000 ^44^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Chee, 2003 ^45^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Chiang, 2021 ^46^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS
Daly, 2006 ^47^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS
Maersk, 2012 ^48^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Rosado, 2011 ^49^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Ting, 2007 ^50^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH
Wagner, 2007 ^51^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.31462531 )

Table 21 Risk of bias for observational studies examining dairy milk and milk alternative consumption in adults and older adults and body composition and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Babio, 2015 ^52^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Bes-Rastrollo, 2008 ^53^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Beydoun, 2018 ^54^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Chen, 2009 ^55^ | LOW | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Drapeau, 2004 ^56^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Duffey, 2010 ^57^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Funtikova, 2015 ^58^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Guerendiain, 2018 ^59^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Guo, 2018 ^60^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Hasselbalch, 2010 ^61^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Holmberg, 2013 ^62^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Johansson, 2018 ^63^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kaikkonen, 2015 ^64^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Kim, 2017 ^65^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Konieczna, 2019 ^66^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | VERY HIGH | LOW | SOME CONCERNS | VERY HIGH
Lee, 2020 ^67^ | HIGH | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Mozaffarian, 2011 ^68^ | HIGH | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Pan, 2013 ^69^ | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Pereira, 2002 ^70^ | LOW | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | SOME CONCERNS
Rautiainen, 2016 ^71^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Romaguera, 2011 ^72^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Rosell, 2006 ^73^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Shin, 2013 ^74^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Smith, 2015 ^75^ | HIGH | LOW | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Snijder, 2008 ^76^ | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Trichia, 2020 ^77^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Vergnaud, 2008 ^78^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Wang, 2014 ^79^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 22 Evidence examining the relationship between dairy milk and milk alternative consumption in individuals during pregnancy and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Intervention/Exposure, Comparator, and Outcome | Results | Confounding and Study Limitations
Randomized controlled trials
Guilloty, 2015 ^85^; PCS, Puerto Rico Testsite for Exploring Contamination Threats (PROTECT), U.S. (Puerto Rico); Analytic N=160; Participant characteristics at baseline:; Puerto Rican individuals during pregnancy; - Age: Mean (SD) = 27.4 (5.3) y; - Female: 100%; - Race/ethnicity: NR; - SEP: Education: 84% > high school, 16%≤ high school; Income: 40% <$20,000 family annual income (poverty threshold for 2012 in Puerto Rico), 60% ≥$20,000. 14% non-response rate for income reporting.; - Anthropometry: Pre-pregnancy BMI: 6% Underweight, 50% Normal weight, 25%; Overweight, 19% Obesity; - Physical activity: NR; - Smoking: NR; - Alcohol intake: NR; - Hx of T2D:; - TEI: NR; - Study beverage intake at baseline: Milk <1x/day ~79%; Included: Healthy pregnant women 18– 40y, living in northern karst region of Puerto Rico, planning to give birth in one of the three participating hospitals, having less than 20 wk gestation, no pregnancy complications, completion of FFQ.; Excluded: pre-pregnancy use of birth control pills; pregnancy conceived by use of assistive reproductive technology; and conditions or complication such as diabetes, hypertension, or heart disease. | Exposure: Milk consumption; No information on fat or sweetener content and unclear if "Milk" also included dairy alternatives. Serving size NR.; Other exposures: coffee, 100% fruit juice, soft drinks, fruit drinks; Comparator: Categorical intake (<1x/d, ≥1x/d); Assessment methods and timing:; Validated, self-administered, semi-quantitative FFQ; represents intake during previous 12mo; Between second and third prenatal visit (20–28wk); Outcomes and assessment methods:; GWG calculated from difference between last and initial weight (first prenatal visit at 16–20wk) recorded in medical record.; Participants were classified as “inadequate GWG” if weight gain was below, “appropriate GWG” if weight gain was according, and “excessive GWG” if weight gain was above the IOM 2009 guidelines. Pre-pregnancy BMI determined by screening visit measurements (<16wk gestation); Last prenatal visit before delivery | [underlined: Gestational weight gain], by frequency of milk intake, Chi-square difference; Total Sample; Excessive GWG: 20.3% <1x/d vs 40.0% ≥1x/d; Appropriate GWG: 52.8% <1x/d vs 40.0% ≥1x/d; Inadequate GWG: 26.8% <1x/d vs 20.0% ≥1x/d; P=0.06; [underlined: Stratified by pre-pregnancy BMI (Under & Normal weight)]:; Excessive GWG: 9% <1x/d vs. 25% ≥1x/d; Appropriate GWG: 58.2% <1x/d vs. 50% ≥1x/d; Inadequate GWG: 32.8% < 1x/d vs. 25% ≥1x/d; P=0.10; [underlined: Stratified by pre-pregnancy BMI (Overweight and Obesity)]:; Excessive GWG: 33.9% <1x/d vs. 60% ≥1x/d; Appropriate GWG: 46.4% <1x/d vs. 26.7% ≥1x/d; Inadequate GWG: 19.6% < 1x/d vs. 13.3% ≥1x/d; P=0.09 | Model adjustments:; - TEI: no; - Key confounders: sex, anthropometry at baseline, diabetes mellitus in the current pregnancy (exclusion criteria), hypertensive disorders in the current pregnancy (exclusion criteria); - Other: N/A; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, socioeconomic position, physical activity, smoking, diet quality, parity; - Exposure not well defined; Exposure data only measured once; Low response rate for completing and returning FFQ, differences in FFQ completers vs. non-completers (completers were younger and with higher education and income); No preregistered data analysis plan; Funding:; Superfund Research for the National Institute of Environmental Health Sciences; RCMI Clinical Research Center; Center for Collaborative Research in Health Disparities; Puerto Rico Clinical and Translational Research Consortium; NIH Institute of Minority Health and Health Disparities
Olaffsdottir, 2006 ^84^; PCS, Iceland; Analytic N=406; Participant characteristics at baseline: Pregnant, Caucasian Icelandic women; - Age: ~28y; - Female: 100%; - Race/ethnicity: All Caucasian; - SES: NR; - Anthropometry: 39% with overweight or obesity at beginning of pregnancy Baseline weight, Mean (SD); Suboptimal GWG: 66 (14) kg; Optimal GWG: 69 (13) kg; Excessive GWG: 74 (11) kg, P <0.001; - Physical activity: NR; - Smoking: NR; - Diet quality: ~14% of total energy intake from added sugars.; - TEI: NR; - Study beverage intake at baseline: NR; Included: Participants were Caucasian women giving birth to full-term babies.; Excluded: miscarriage or stillbirth, pregnant with twins or triplets, preterm birth, missing data (including FFQ and lifestyle questionnaires) | Exposure: Drank more milk during early or late pregnancy compared with usual intake before pregnancy; details NR; Other exposures: SSB; Comparator: Did not drink more milk during early or late pregnancy compared with usual intake before pregnancy; Assessment methods and timing: Lifestyle questionnaire with multiple choice questions on changes in eating patterns in early and late pregnancy compared with usual intake before pregnancy (yes/no answer) 11–15 wk gestation (early pregnancy), 34–37 wk gestation (late pregnancy); Outcomes and assessment methods:; - GWG estimated by subtracting weight at first visit at 11–15 weeks gestation from last weight measurement before delivery. • GWG was divided into groups of suboptimal, optimal and excessive weight gain, according to recommendations based on Icelandic studies on maternal weight gain. Optimal weight gain: 12.1–18.0 kg for prepregnantly normal-weight women and 7.1–12.0 kg for overweight women.; - Measured 11–15 weeks gestation; last weight measurement before delivery | [underlined: Optimal or Excessive GWG] when drinking more milk late in pregnancy, OR (95% CI), logistic regression; Suboptimal GWG: ref; Optimal+Excessive GWG: 3.10 (1.57, 6.13), P=0.001; [underlined: Excessive GWG] when drinking more milk late in pregnancy, OR (95% CI), logistic regression; Suboptimal+Optimal GWG: ref; Excessive GWG: 1.82 (1.08, 3.06), P=0.024; Drinking more milk early in pregnancy, all results = NS | Model adjustments:; - TEI: no; - Key confounders: sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, smoking, physical activity, parity; - Other: Gestational length, fetal sex; Limitations:; - Did not account for key confounders: diet quality, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Exposure not well defined; No preregistered data analysis plan; Funding:; Icelandic Research Council; University of Iceland Research Fund

a BMI: body mass index; CI: confidence interval; d: day(s); FFQ: food frequency questionnaire; g: gram(s); GWG: Gestational weight gain; HAZ: height-for-age z-score; hr: hour; HR: hazard ratio; kcal: kilocalorie(s); kg: kilogram(s); L: liter; m: meter(s); mg: milligram(s); min: minute(s); mL: milliliter(s); N/A: not applicable; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NR: not reported; NS: not significant; OR: odds ratio; PCS: prospective cohort study; REF: reference group; SD: standard deviation; SE: standard error; SEP: Socioeconomic position; SSB: sugar-sweetened beverage(s); svg: serving(s); TEI: total energy intake; wk: week(s); y: year(s)

Table 23 Risk of bias for observational studies examining dairy milk and milk alternative consumption in individuals during pregnancy and body composition and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Guilloty, 2015 ^85^ | HIGH | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | HIGH
Olafsdottir, 2006 ^84^ | HIGH | HIGH | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.