# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 5 systematic reviews assessing the relationship between beverage consumption (beverage patterns, dairy and milk alternatives^†^; 100% juice^‡^; low- and no-calorie sweetened beverages^§^; and sugar sweetened beverages^**^) and growth, body composition, and risk of obesity. The literature searches yielded 36,223 search results after the removal of duplicates (Figure 2). Dual-screening resulted in the exclusion of 33,121 titles, 2,552 abstracts, and 463 full-texts articles. Reasons for full-text exclusion are in Appendix 5. One hundred sixty-seven additional articles were identified from existing reviews, and two additional milk articles were identified from the manual search. The body of evidence examining dairy milk and milk alternatives included 85 articles. Some articles include data for more than one of these categories.

† Raynor HA, Deierlein AL, Gardner CD, . Dairy Milk and Milk Alternatives and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR03

‡ Deierlein AL, Raynor, HA, . 100% Juice and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review Available at: 10.52570/NESR.DGAC2025.SR05

§ Raynor HA, Deierlein AL, Anderson CAM, . Low- and No-Calorie Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR04

** Deierlein AL, Raynor HA, Andres A, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR23

- Children and adolescents: 43 articles
  ▪ Total milk: 34 articles
  ▪ Milk by fat content: 11 articles
  ▪ Milk by sweetener content: 3 articles
  ▪ Milk alternatives: 1 article
- Adults and older adults: 40 articles
  ▪ Total milk: 25 articles
  ▪ Milk by fat content: 14 articles
  ▪ Milk by sweetener content: 0 articles
  ▪ Milk alternatives: 1 article
  ▪ Mendelian randomization studies: 4 articles
- Individuals during pregnancy and postpartum: 2 articles

Figure 2 Literature search and screen flowchart

The literature searches in PubMed, Embase, Cochrane, and CINAHL, retrieved 36,223 records after removing duplicates. 167 were included from existing reviews. 38 were found with manual search methods. 33,121 titles, 2,552 abstracts, and 463 full-texts were excluded. 292 articles were included across the five systematic reviews examining beverage consumption and growth, body composition, and risk of obesity.

## Children and adolescents

The body of evidence examining the relationship between dairy milk and milk alternatives and growth, body composition, and risk of obesity in children and adolescents included 43 articles. Five of the 43 studies were randomized controlled trials (RCT) from three independent trials, two were non-randomized controlled trials (NRCT), and the remaining 36 were prospective cohort studies (PCS). Evidence for this population is summarized in Table 15.

The interventions and exposures assessing intake of dairy milk or milk alternatives in children and adolescents fell into four categories: total milk (5 RCTs, 1 NRCT, 28 PCS), milk stratified by fat content (11 PCS), milk stratified by sweetener content (3 PCS), and milk alternatives (1 NRCT). The evidence was synthesized according to these categories. Most evidence fell in the first two categories, and some studies contributed data to more than one category.

### Total milk

#### Description of the evidence

##### Population

Thirty-four articles examined total milk intake, including five RCTs,^1–5^ one NRCT,^6^ and 28 PCS.^7–34^ One RCT was conducted in the United States (U.S.),^2^ one in Denmark, (represented by three articles^1,3,4^), and one in Iran.^5^ The NRCT was conducted in the U.S.^6^ Sample sizes ranged from N=66 to N=469. All but one trial enrolled participants with ages ranging from 12–15 years, with a single study enrolling children age eight on average^5^. All trials reported >50% female participants, and one enrolled females exclusively.^6^ Two trials had inclusion criteria around participant BMI: one enrolled participants with age-adjusted BMI >25 kg/m^2^, and the second enrolled participants with BMI >50^th^ and ≤99^th^ percentiles. Race and/or ethnicity data were reported for all but one RCT.^5^ Two trials reported the sample was ≥95% white participants,^1,3,4,6^ and one reported an 86% “Minorities” sample.^2^ The study conducted in Iran did not report data on race and/or ethnicity.^5^ Data on socioeconomic position were provided in only one study, and it reported that the region that study was conducted in was medium SEP and roughly one quarter of participant homes had separate rooms for children.^5^

Seventeen of the 28 PCS were conducted in the U.S., three in Australia,^21,31,32^, two in the United Kingdom (U.K.),^19,28^ two in Denmark,^33,34^ and one each in Canada,^13^ Hong Kong,^23^ Portugal,^24^ and South Korea.^11^ Sample sizes ranged from N=49 to N=26,047. Multiple U.S. cohorts were represented by more than one article in this body of evidence: four articles came from the Growing Up Today Study,^7–9,29^ two came from the Avon Longitudinal Study of Parents and Children,^19,28^ and two came from the Iowa Fluoride and Iowa Bone Development Studies.^25,26^

The larger number of PCS provided a greater distribution of participant age, with roughly half of the studies in children and half in adolescents. The average baseline age across studies ranged from 2 to 13 years, with the possible age range going up to 16 years in one study.^29^ Thirteen articles reported participants had an average age in the 2–5-year range,^11,12,14,15,17–21,25–27,33^ and the remaining 15 reported participants were age 8–14 years.^7–10,13,16,22–24,28–32,34^ Most studies enrolled roughly half female participants, and three exclusively enrolled females.^7,15,30^ Most cohorts consisted of predominantly white participants ^7–10,12,15–18,20,25–27,29,35^. One reported >50% Black participants30, and one reported >20%.^14^ Four articles reported ≥20% Hispanic participants^12,14^ or Asian participants.^16,23^ The remaining eight articles did not provide information on race and/or ethnicity. The most common metrics used across cohorts to measure socioeconomic position (SEP) were parental education and household income. Ten articles did not report SEP. Of those that did, six consisted of a predominantly lower SEP population,^14,23,24,27,30,34^ while 11 consisted of a roughly even distribution of low-, middle-, and high-SEP,^11,12,15–17,21,25,26,28,32,33^ and one reported a predominantly higher-SEP population.^18^ No PCS had eligibility criteria around baseline anthropometrics. Rates of overweight/obesity across cohorts ranged from 0–32%.

##### Intervention/Exposure

The type and amount of milk used in the trials varied substantially. In one trial, participants were randomized to one liter per day of skim milk for 12 weeks;^1,3,4^ in another participants consumed three, eight-ounce servings of 1% milk plus resistance training for 12 weeks;^6^ in one participants consumed 24 ounces (oz) per day of fat-free chocolate milk and 1% plain milk plus resistance training for six months;^2^ and in the fourth, participants consumed 250 milliliters (mL) per day of 2% milk for three months.^5^ Only one of the four trials instructed participants to substitute the milk intake for a nondairy source of equal energy (preferably sugar-sweetened beverages); the other three did not provide any instruction around compensatory energy intake. No trials reported issues with adequate compliance.

Roughly half of the PCS measuring total milk intake stated they were looking at dairy milk, specifically; while the other half did not provide this specification, so it cannot be determined if their exposure is limited to dairy milk or also includes milk alternatives. Most studies noted that their total milk exposure included sweetened milk intake. Intake was measured using food frequency questionnaires (FFQ) in 12 articles,^7–9,16,18,21,23–2^,^7,29^ multiple day records in 8,^17,19,20,28,30,31,33,36^ 24-hour dietary recalls in 5,^10,13,15,32,34^ and short questionnaires in 4.^11,12,14,22^

##### Comparator

The RCTs compared the active milk intervention group to either a non-intervention control group, a water condition, or a resistance training group. Lambourne^2^, whose intervention included 24 oz/d of skim chocolate and 1% plain milk plus resistance training included a comparison group of equivalent water intake (24 oz/d) plus resistance training. Another trial included a 1L/d water control group compared to the 1L/d skim milk intervention group.^1,3,4^. The final independent RCT compared 2% dairy milk (250 mL/d) to a non-intervention control group.^5^ The NRCT compared two milk intervention groups (24 oz/d or 24 oz/d plus resistance training) to resistance training only and to a non-intervention control.^6^

The PCS examining total milk consumption all compared varying levels of total milk intake. No studies compared total milk intake to water. Twenty-four of the 28 PCS articles examined continuous milk intake, four of those also looked at categorical intake,^9,12,24,27^ and four examined categorical intake only.^7,11,1^,^7,23^ The categories and metrics used for the latter varied minimally across studies and tended to reflect the spectrum of daily intake from <1 serving per day up to >3 servings per day.

##### Outcome

Studies examining total dairy milk and milk alternative consumption in children and adolescents examined a variety of outcomes in the broad buckets of growth, body composition, and risk of obesity. All PCS had a follow-up period of at least one year, and most cohorts were followed for five years or longer. Six PCS utilized self-reported outcome data,^7–9,13,16,3^,^7^ but the remaining studies used outcomes measured by either health professionals or trained study staff. Across the evidence, unadjusted BMI and weight data were deprioritized in synthesis since these measures should be adjusted for sex and age in children and adolescents.

The RCTs and NRCT most commonly measured body composition outcomes, namely waist, mid-arm, and hip circumference^1–6^; fat mass^1–4,6^; and lean mass.^1–4,6^ Growth metrics of BMI,^1–4^ and height were frequently measured, as well. No trial looked at risk of obesity measures. Three trials were 12 weeks in duration,^1,3–5^ one was six months,^2^ and one ran a full year.^38^

For both younger children (age 2–5y) and older children and adolescents (age 8y+), the main outcome examined across PCS was age- and sex-adjusted BMI percentile or BMI z-scores; in total, 18 articles examined adjusted BMI.^8–11,14,16,1^,^8,21–24,26,29,32–34^ Other indicators of growth, such as height, were measured in 3 articles.^7,12,25^ Body composition was most commonly evaluated using fat mass^15,17,19,28,32,34^ and waist circumference.^17,20,34^ Overweight and/or obesity incidence was measured in the 5 articles that assessed risk of obesity.^9,11,12,16,21^

#### Synthesis of the evidence

The evidence in children and adolescents fell cleanly into 2 categories: those enrolling participants aged 2–5 years and those enrolling older children through adolescents (typically in the 8–16 year age range). Therefore, the evidence was synthesized according to these age groups. Additionally, due to the impact of energy intake on the relationship between milk consumption and outcomes of growth, body composition, and risk of obesity, studies were grouped by whether or not they accounted for TEI during synthesis discussions. Lastly, as noted previously, unadjusted BMI and weight data were deprioritized in the synthesis of childhood and adolescent data. The studies included in this body of evidence are summarized in Table 15, with their risk of bias assessments summarized in Table 16, Table 17, and Table 18.

As noted, the 34 studies fell into 2 categories based on participant age, with the RCTs, NRCT, and roughly half of the observational studies enrolling older children and adolescents, while the other observational studies focused on younger children in the 2–5 year age range. Most studies followed participants over 1 to 4 years, though some tracked participants up to 10 years.

Thirteen PCS examined total milk intake in younger children aged 2–5 years. Findings were split between showing a beneficial relationship between total milk intake and favorable growth, body composition, or risk of obesity, or null relationships. For studies that adjusted for energy intake, all significant findings showed a beneficial association between total milk intake and increased height,^25^ decreased waist circumference gain,^20^ decreased body fat,^17^, or decreased fat mass gain.^19^ The study that found a beneficial association with body fat did conversely find a null relationship with waist circumference and BMI.^17^ Studies examining BMI (typically BMI z-scores) found null relationships with total milk intake.^17,18,26,27,33^ The PCS that did not adjust for energy intake tended to find null associations, though one study found that lower milk intake levels was associated with increased obesity incidence while the highest intake level was not.^11^ Another study found total milk intake was associated with increased height-for-age z-score but not with BMI, weight-for-height z-score or overweight/obesity incidence.^12^

Across the PCS examining total milk intake in younger children aged 2–5 years, a substantial number of studies found an association between increased intake and favorable outcomes; however, many studies found no association. This evidence was limited by a lack of trial data.

The evidence in older children and adolescents was even more inconsistent and impacted by additional methodological limitations. The trials found either a mix of detrimental and null effects or exclusively null effects; however, no trial accounted for the additional energy intake created by the addition of milk to the diet. Three trials found unfavorable fat mass changes in the intervention group compared to a water^1–4^ or non-intervention control,^5^ though this effect was limited to only girls in one study^5^ and only boys in another.^2^ BMI was examined in two trials, one of which found higher BMI z-scores in the intervention group^1,3,4^ while the other found no effect.^2^ All findings for height, waist circumference and lean mass were non-significant.^1–4,6^

The observational data tended toward null associations across studies, though there were significant findings in both directions in the studies that adjusted for energy intake. Four PCS found a beneficial relationship between increased milk intake and outcomes of body fat percentage,^28^ height,^7,8^ and overweight incidence at follow up.^16^ One study conversely found greater milk intake related to increased BMI at follow up. Of the PCS that did not adjust for energy intake, all found null associations with the outcomes of interest, which were limited in those studies to BMI and weight.

The trials in older children and adolescents did not account for energy intake, which substantially compromised the ability to parse apart the effects of the energy from the effects of the milk itself. As a result, they showed results that were opposite in direction from the observational findings. Furthermore, the PCS in this population were also inconsistent in the direction and magnitude of findings, limiting the ability to synthesize or draw any conclusions.

#### Conclusion statements and grades: Total milk

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements to answer the question “What is the relationship between dairy milk and milk alternative consumption and growth, body composition, and risk of obesity?” based on their review of the evidence. The conclusion statements and grades specific to total milk intake by children and adolescents are documented below in Table 5.

Table 5 Conclusion statements and grades for total milk and growth, body composition, and risk of obesity in children and adolescents

Conclusion Statement | Total milk consumption by younger children may be associated with favorable growth and body composition, and lower risk of obesity during childhood. This conclusion statement is based on evidence graded as limited. | A conclusion statement cannot be drawn about the relationship between total milk consumption by older children and adolescents and growth, body composition, and risk of obesity because of substantial concerns with directness, consistency, and risk of bias in the body of evidence.
Grade | Limited | Grade Not Assignable
Body of Evidence | 13 PCS | 5 RCTs, 1 NRCT, 15 PCS
Consistency | Some concerns with inconsistency in the direction of findings | Rationale:; - Trials did not account for energy intake when comparing the addition of milk to water or a non-intervention control; - Observational studies were highly variable in exposure and comparator definitions and found a mix of null, positive, and negative associations; Several studies had a high risk of bias across multiple domains
Precision | Substantial concerns due to smaller sample sizes and varying metrics across studies
Risk of bias | Substantial concerns, particularly risk of bias due to confounding and missing data
Directness | Few concerns with directness
Generalizability | Substantial concerns with generalizability due to minimal racial and/or ethnic diversity

##### Assessment of the evidence: Total milk

The body of evidence underlying the conclusion statement for total milk consumption in younger children consisted of 13 PCS in children aged 2–5 years. The strength of evidence was graded using the five grading elements summarized below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence included both large and small studies, including small studies with null findings, so there was less concern of publication bias.

###### Consistency

There were some concerns with inconsistency in the direction of findings. Studies with significant findings all showed a beneficial association between increased total milk intake and favorable growth, body composition, and risk of obesity outcomes. However, a large proportion of the studies showed null results.

###### Precision

There were substantial concerns with precision due to smaller sample sizes in the RCTs and multiple PCS. Studies also varied substantially in the metrics used to define and measure milk intake, limiting comparability across them.

###### Risk of bias

There were substantial concerns with risk of bias, particularly bias due to lack of adjustment for key confounders and lack of appropriately accounting for missing data (Table 16, Table 17, & Table 18).

###### Directness

There were few concerns with directness. All RCTs targeted this research question, and though many PCS had a broader research purpose, there were no concerns about bias due to lack of directness.

###### Generalizability

There were substantial concerns with generalizability due to minimal racial and/or ethnic diversity across the body of evidence. Roughly one third of studies did not report data on race and/or ethnicity, and of those that did, all but one consisted of predominantly non-Hispanic white children. Most studies enrolled participants with a range of SEP, but no studies exclusively enrolled a lower-SEP sample.

### Milk by fat content

#### Description of the evidence

##### Population

Eleven PCS examined the consumption of milk by fat content. Seven were conducted in the U.S.,^12,14,18,29,35,39,40^ two in Canada,^13,41^ and two in the U.K..^28,36^ Sample sizes ranged from 30413 to 8,173.^29^ The Early Childhood Longitudinal Survey^12,39^ and Project Viva^18,35^ cohorts were each represented by two articles in this body of evidence. Average participant age ranged from 2 to 13 years, with one study enrolling participants up to age 18.^40^ Six studies enrolled participants under age five.^14,18,35,39,41^ All cohorts enrolled roughly half female and half male participants.

Nine articles reported data on race and/or ethnicity, and of those, 8 were predominantly white participants.^12,18,28,29,35,39–41^ Three were ≥20% Hispanic,^12,14,39^ and two were >20% Black participants.^14,40^ Seven articles reported on SEP, primarily through parental education, household income, or a multi-component SEP metric. One study consisted of predominantly participants with a lower SEP,^14^ three showed roughly even distribution across SEP,^12,28,39^ and three consisted of a higher-SEP population.^18,35,41^ No PCS had eligibility criteria around baseline anthropometrics. Rates of overweight/obesity across cohorts ranged from 0–44%.

##### Intervention/Exposure

No trials were available that directly compared the effects of different levels of fat in milk on growth, body composition, or risk of obesity outcomes. However, 11 PCS examined intake of milk stratified by fat content. Six of these also looked at total milk intake and are included in both bodies of evidence.^12–14,18,28,29^ There was substantial variability in how studies grouped the different milk fat levels. The most common approach was to group the lower-fat milks (skim/1%) and the higher-fat milks (2%/whole).^13,14,29,35,36,39^ Other studies examined skim, 1%, 2%, and whole milks independently,^12,41^ while others grouped 1% and 2% milk together,^28^ skim and 1%,^35^ or all reduced-fat milks together, leaving whole milk as a separate category.^40^

Intake was measured using an FFQ,^18,29,35^ 24-hour recall,^13^ multiple-day food record,^36,42^ or short questionnaire.^12,14,39–41^

##### Comparator

For different types of milk by fat content, the comparator tended to be continuous intake within each milk type. A small number of studies examined categorical intake, and those categories varied in whether they measured a broader frequency of intake or more specific servings/glasses per day.

##### Outcome

Studies examining dairy milk and milk alternative consumption by fat content in children and adolescents examined a variety of outcomes spanning growth, body composition, and risk of obesity. All PCS had a follow-up period of at least one year, and most cohorts were followed for five years or longer. Two studies utilized self-reported outcome data,^13,29^ but the remaining studies used outcomes measured by either health professionals or trained study staff. Across the evidence, unadjusted BMI and weight data were deprioritized in synthesis since these measures should be adjusted for sex and age in children and adolescents.

The most common outcome measured in the studies assessing milk by fat content was BMI z-scores. Seven articles examined this growth outcome,^12,14,18,35,39–41^ and 1 also measured adjusted weight and height.^12^ Incidence of overweight and obesity was measured in four articles,^35,39–41^ and the body composition measures of waist circumference, fat mass, lean mass, or sum of skinfolds were examined in an additional two articles.^28,35^

#### Synthesis of the evidence

The evidence on milk by fat content in children and adolescents also fell cleanly into two categories: those enrolling participants aged 2–5 years and those enrolling older children through adolescents (typically in the 8–16-year age range). Therefore, the evidence was synthesized according to these age groups. Additionally, due to the impact of energy intake on the relationship between milk consumption and outcomes of growth, body composition, and risk of obesity, studies were grouped by whether they accounted for TEI during synthesis discussions. Lastly, as noted previously, unadjusted BMI and weight data were deprioritized in the synthesis of childhood and adolescent data. The studies included in this body of evidence are summarized in Table 15, with their risk of bias assessments summarized in Table 18.

As with the studies in total milk, the 11 PCS examining milk stratified by fat content divided into those looking at younger children and those looking at older children and adolescents. The six studies in younger children consistently found a beneficial association between increased whole or higher-fat milk intake and favorable growth, body composition, or risk of obesity outcomes. Two articles from the same cohort found increased whole milk or whole+2% milk was associated with decreased BMI z-score in the shorter-term follow-up (1 year) and waist circumference and overweight/obesity prevalence over both shorter- and longer-term follow-up (10 years), though the BMI findings were no longer significant at 10 year follow-up.^18,35^. Another found lower BMI z-score, overweight, and obesity prevalence over 3 years with greater whole milk intake compared to lower fat milks.^41^ An additional study found favorable BMI, weight-for height, and height-for-age z-scores with each 1% increase in milk fat.^12^ Another did not show an association with BMI z-score but did find decreased overweight/obesity prevalence over 2 years with greater whole+2% milk intake. Only one study had exclusively null findings, finding no relationship with whole+2% milk intake and BMI z-scores. All studies also looked at lower-fat milk intake individually, but there were no significant associations between lower-fat milk and growth, body composition or risk of obesity across the body of evidence.

The five PCS in older children and adolescents contained a substantial amount of unadjusted outcome data, which were deprioritized for synthesis. Not including those data, one study found a detrimental association with overweight/obesity prevalence for children who did not change from higher to lower fat milk from intake at age 10 to follow up 2 years later.^40^ Another found no association across milk fat types and body fat percentage at 1-year follow up or 3-year follow up.^28^ Overall, the evidence was scarce and inconsistent in this older population.

No trials were available that directly compared the effects of different levels of fat in milk on growth, body composition, or risk of obesity outcomes, which impacted the Committee’s ability to draw firm conclusions. The observational evidence in younger children was consistent in direction of association. However, in older children and adolescents, the evidence was much more inconsistent and difficult to synthesize.

#### Conclusion statements and grades: Milk by fat content

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements to answer the question “What is the relationship between dairy milk and milk alternative consumption and growth, body composition, and risk of obesity?” based on their review of the evidence. The conclusion statements and grades specific to milk by fat content in children and adolescents are documented below in Table 6.

Table 6 Conclusion statements and grades for milk by fat content and growth, body composition, and risk of obesity in children and adolescents

Conclusion Statement | Consumption of higher-fat dairy milk compared to lower-fat dairy milk by younger children may be associated with favorable growth and body composition, and lower risk of obesity during childhood. This conclusion statement is based on evidence graded as limited.
Grade | Limited
Body of Evidence | 6 PCS
Consistency | Some concerns with inconsistency in findings, though all were either positive or null
Precision | Substantial concerns due to the small number of studies and varying metrics across them
Risk of bias | Substantial concerns, particularly risk of bias due to confounding and missing data
Directness | Some concerns due to a lack of direct trial data
Generalizability | Few concerns with generalizability to the US population
Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of milk with different fat content by older children and adolescents and growth, body composition, and risk of obesity because of substantial concerns with consistency, quantity, and risk of bias in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 5 PCS
Rationale | - The number of eligible studies was small; - Multiple studies utilized unadjusted outcome data; - Exposure definitions varied substantially, and findings were mixed; - Several studies had a high risk of bias across multiple domains

##### Assessment of the evidence

The body of evidence underlying the conclusion statement for milk by fat content in younger children consisted of six PCS in children aged 2–5 years. The strength of evidence was graded using the five grading elements detailed below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence includes both large and small studies, including small studies with null findings, so there was less concern of publication bias.

###### Consistency

There were some concerns with inconsistency in findings, though as with total milk, all were either positive or null. Studies showing an association between milk by fat content and the outcomes of growth, body composition, and risk of obesity all showed a favorable association between greater intake of higher-fat milks and favorable growth, body composition, and risk of obesity outcomes in younger children (age 2–5y).

###### Precision

There were substantial concerns with precision due to the small number of studies in this body of evidence and varying exposure metrics across them.

###### Risk of bias

There were substantial concerns with risk of bias, particularly potential bias caused by lack of adjustment for key confounders and lack of appropriately accounting for missing data (Table 16, Table 17, & Table 18).

###### Directness

There were some concerns with directness due to a lack of direct trial data. There were no available trial data directly comparing milk by different fat content and the impact on these outcomes of interest. All data were observational.

###### Generalizability

There were few concerns with generalizability to the US population due to good representation across racial and ethnic groups, SEP, and sex.

### Milk by sweetener content

#### Description of the evidence

##### Population

No trials were available that directly compared the effects of sweetened vs. unsweetened milk on growth, body composition, or risk of obesity outcomes. However, 3 PCS examined milk by sweetener content. The studies included in this body of evidence are summarized in Table 15, with their risk of bias assessments summarized in Table 18. Two were conducted in the U.S.^37,43^ and one in the U.K.^42^ Sample sizes ranged from N=91 to N=2,294. All studies enrolled roughly half female and half male participants. The average age ranged from 10–15 years. Two studies consisted of predominantly white participants^37,42^ while the third reported 63% Black participants and 33% white.^44^ SEP was not reported or was unclear for two of the three cohorts,^37,43^ and the third reported a primarily higher-SEP sample based on maternal education level.^42^ Wrotniak et al^43^ exclusively enrolled an obesity treatment-seeking sample. The other two cohorts had no anthropometric eligibility criteria, and the one that reported baseline data showed an overweight/obesity prevalence of 21%.^42^

##### Intervention/Exposure

Noel et al^42^ looked at flavored milk consumers and non-consumers, Vanselow et al^37^ assessed plain milk and chocolate milk consumption independently, and Wrotniak et al^43^ examined flavored and unflavored milk intake independently. Intake was measured using a 3-day dietary record^42,43^ or an FFQ.^37^

##### Comparator

The three PCS that measured consumption of sweetened milk compared it to varying levels of consumption^37,43^ or to no consumption.^42^

##### Outcome

Two of the three studies examining milk by sweetener content measured BMI change. The outcomes of body fat, normal weight status, and weight change were each measured in a single study.

##### Synthesis of the evidence

Unadjusted BMI and weight data were deprioritized in the synthesis of childhood and adolescent data.

Three PCS looked at milk by sweetener content, and all were in an adolescent population. Once unadjusted outcome data were deprioritized, all remaining findings were null. The three studies looked at outcomes of fat mass,^42^ BMI z-score,^43^ and BMI change^37^ and consistently found a lack of association with sweetened milk intake.

##### Conclusion statements and grades: Milk by sweetener content

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements to answer the question “What is the relationship between dairy milk and milk alternative consumption and growth, body composition, and risk of obesity?” based on their review of the evidence. The conclusion statements and grades specific to milk by sweetener content in children and adolescents are documented below in Table 7.

Table 7 Conclusion statements and grades for milk by sweetener content and growth, body composition, and risk of obesity in children and adolescents

Conclusion Statement | There may not be a relationship between consumption of sweetened milk by older children and adolescents and growth, body composition, and risk of obesity. This conclusion statement is based on evidence graded as limited. | A conclusion statement cannot be drawn about the relationship between consumption of sweetened milk by younger children and growth, body composition, and risk of obesity because there is no evidence available.
Grade | Limited | Grade Not Assignable
Body of Evidence | 3 prospective cohort studies | 0 articles
Consistency | Some concerns with inconsistency in direction of findings | Rationale: No articles met the inclusion criteria
Precision | Substantial concerns due to the small number of studies and varying metrics across them | Rationale: No articles met the inclusion criteria
Risk of bias | Some concerns, particularly risk of bias due to missing data | Rationale: No articles met the inclusion criteria
Directness | Some concerns with directness | Rationale: No articles met the inclusion criteria
Generalizability | Substantial concerns in generalizability to the US population | Rationale: No articles met the inclusion criteria

###### Assessment of the evidence

The body of evidence underlying the conclusion statement included 3 prospective cohort studies, and all had an average age of 10 years or older. The strength of that evidence was graded based on an assessment of the five grading elements, as described below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. Publication bias is always a concern, and with this small of a body of evidence, it is difficult to assess. This body of evidence did include both small and larger studies, including studies with only null findings.

###### Consistency

There were some concerns with inconsistency in the direction of findings. De-prioritization of unadjusted outcome data reduced concerns with inconsistency, but it also substantially reduced the size of the body of evidence.

###### Precision

There were substantial concerns due to the small number of studies and varying definitions of the exposures and the metrics used to measure them.

###### Risk of bias

There were some concerns with risk of bias, particularly risk of bias due to unaccounted for missing data (Table 18).

###### Directness

There were some concerns with directness due to a lack of trial data. All data were observational.

###### Generalizability

There were substantial concerns in generalizability to the US population, primarily due to the very small body of evidence. Two of the three studies consisted of higher SEP, primarily non-Hispanic white participants, and the third consisted of >60% Black participants but did not report SEP.

### Milk alternatives

#### Description of the evidence

##### Population

The single study examining consumption of milk alternatives, independently, was an NRCT conducted in Hong Kong.38 This trial enrolled a sample of 210 female Chinese participants with a mean baseline age of 15 years. Data on SEP were not reported. The study is summarized in Table 15, and its risk of bias assessment is summarized in Table 18.

##### Intervention/exposure and Comparator

In the NRCT on milk alternatives, participants consumed 375 mL/d calcium-fortified soymilk for 12 months, which was compared to a non-intervention control group.^38^

##### Outcome

The NRCT targeting soymilk examined the outcomes of height, weight, and BMI.^38^

#### Synthesis of the evidence

The NRCT that looked soymilk compared to a non-intervention control found no significant between-group differences in height, weight, or BMI.^38^

#### Conclusion statement and grade: Milk alternatives

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question “What is the relationship between dairy milk and milk alternative consumption and growth, body composition, and risk of obesity?” based on their review of the evidence. The conclusion statement and grade specific to milk alternative consumption by children and adolescents is documented below in Table 8.

Table 8 Conclusion statement and grade for milk alternatives and growth, body composition, and risk of obesity in children and adolescents

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of milk alternatives by children and adolescents and growth, body composition, and risk of obesity because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 non-randomized controlled trial
Rationale | There was only one eligible study examining milk alternative consumption by children and adolescents and growth, body composition, and risk of obesity.

## Adults and older adults

The body of evidence examining the relationship between dairy milk and milk alternatives and body composition and risk of obesity in adults and older adults included 36 articles. Eight of the 36 studies were RCTs from seven unique trials,^44–51^ and the remaining 28 were PCS.^52–79^ Evidence for this population is summarized in Table 19.

Similar to the evidence in children and adolescents, the interventions and exposures assessing intake of dairy milk or milk alternatives in adults and older adults was also synthesized in 4 categories: total milk (8 RCTs, 28 PCS), milk stratified by fat content (14 PCS), milk stratified by sweetener content (0 studies), and milk alternatives (1 RCT). The evidence was synthesized according to these categories; some studies contributed data to more than one category.

Only 1 study, an RCT, exclusively enrolled older adults (i.e., all participants were older than 65 years).^46^ Its purpose and population were substantially different than the other studies in this body of evidence, so its contribution to the synthesis was minimal, and no conclusions could be drawn specific to that population.

### Total milk

#### Description of the evidence

##### Population

The evidence examining total milk intake in adults and older adults consisted of 8 RCTs and 17 PCS. Two trials were conducted in the U.S.,^44,51^ and 1 each in Australia,^47^ Denmark,^48^ Malaysia,^45,50^ Mexico,^49^ and Taiwan.^46^ The trial in Malaysia was represented by two articles.^45,50^ Trial sample sizes ranged from 35^46^ to 200.^44^ There was an imbalance of male and female participants across all trials but one, which enrolled roughly half female, half male participants.^44^ Of the others, three exclusively enrolled female participants,^45,49–51^ and a fourth enrolled >70% females.^48^ One trial exclusively enrolled male participants,^47^ while another enrolled >80% males.^46^ Mean participant age ranged from 34 to 65 years across trials, with possible age ranges across the full adulthood spectrum in three studies^48,49,51^ and limited to middle-aged to older adults in three studies.^44,45,47,50^ One trial – noted earlier – exclusively enrolled older adults over age 78 who had sarcopenia.^46^ Data on race and/or ethnicity were reported in four trials, two of which consisted of >95% white participants^44,47^; one enrolled 100% Chinese,^45,50^ and the fourth enrolled a 100% Mexican sample.^49^ Socioeconomic position was reported by only one study. Barr et al^44^ reported a mean education level of 15 years. Three trials exclusively enrolled participants with overweight or obesity.^48,49,51^

Multiple cohorts were represented by more than one article in the 17 PCS. Cohorts from EPIC were used in two articles^72,77^ and secondary analyses from PREDIMED in two articles.^52,66^ Study sites for the 17 PCS were geographically diverse. Five were conducted in the U.S.,^53–55,70,79^ with a smaller number in Denmark,^72^ Ecuador,^59^ England,^60,72^ France,^78^ Finland,^64^ Germany,^72^ Italy,^72^ the Netherlands,^72,76^ South Korea,^65,67,74^ and Sweden.^63^ Sample sizes ranged from N=31^59^ to N=50,026.^53^ Mean age across cohorts ranged from 25 to 67 years. For those that provided age range at enrollment, most enrolled participants across the full span of adulthood, though a small number enrolled middle-aged to older adults only. One cohort was exclusively female participants,^53^ while another was >80% women, and 1 was exclusively male.^60^

Race and/or ethnicity data were reported in 6 of the 17 articles. Three cohorts consisted of primarily white participants,^55,76,79^ one of 60% black participants,^54^ and another of roughly half white, half Black participants.^70^ The sixth cohort consisted of 100% Korean participants.^67^ SEP was reported in 12 PCS, most commonly by education or occupation. Cohorts tended to have medium SEP with good representation across all SEP tiers. Occupational data reflected a large representation of health professionals and academics, though roughly half of the cohorts had >30% manual workers or participants with lower education. Baseline anthropometry was not used as an eligibility criterion for any cohorts, though one cohort exclusively enrolled participants with prehypertension or stage 1 hypertension at baseline, and 65% of those individuals had obesity.^55^ Otherwise, prevalence of overweight and obesity across cohorts tended to correspond with broader population rates.

##### Intervention/Exposure

The type of milk used in the 8 RCTs in adults was consistent, with all using either skim, 1%, or a combination of the two. Three trials included compensation for energy intake in their design,^45,49–51^ with 1 randomizing participants to 400 mL/d of skim milk with instruction to reduce calories elsewhere,^45,50^ a second adding 750 mL/d of 1% milk as part of an energy-restricted diet,^49^ and the third adding 20 oz/d of 1% milk as part of a prescribed energy-restricted diet where servings of fruit, meat, and starch were removed to compensate for the milk.^51^ The remaining trials added 24 oz/d of skim/1% milk,^44^ 400 mL/d of 1% milk,^47^ or 1 L/d of 1% milk;^48^ they did not include design or instruction to adjust for the extra energy from milk. The remaining trial in older adults with sarcopenia added 400 mL/d combined with mild resistance exercise; it also included a soymilk plus resistance training intervention group. No trials reported issues with adequate compliance.

Similar to the data in children, roughly half of the PCS in adults measuring total milk intake stated they were looking at dairy milk, specifically; the other half did not provide this specification, so it cannot be determined if their exposure is limited to dairy milk or also includes milk alternatives. Intake was measured using an FFQ in 11 studies, 24-hour recalls in three, a short questionnaire in 2, and a three-day dietary record in 1.

##### Comparator

The 8 RCTs used a variety of comparison groups, including a water group,^46,48^ a non-intervention control,^44,45,47,50,51^ and an energy-restricted diet without dairy.^49^ For the three trials that included compensation for energy intake in their design, the Malaysian trial compared the skim milk intervention to a usual diet control,^45,50^ Rosado et al^49^ and Wagner et al^51^ both compared low-fat milk with an energy-restricted diet to an energy-restricted diet that either allowed no dairy,^49^ or included dairy for adequate calcium intake but did not include the additional daily milk of the intervention group. The interventions without energy compensation compared the addition of milk to either a usual diet control^44,47^ or to the addition of water in an equal amount.^46,48^

Eleven of the 17 PCS compared intake across categories,^52,53,59,60,63–65,67,74^ and the remaining six looked at continuous intake.^54,55,70,72,76,77^ Studies varied considerably in how they quantified intake, ranging from recent frequency to number of habitual servings, to metrics such as milliliters per day or grams per day. As a result, the categories used across articles were rarely consistent. Tertiles of intake were the only categorical comparison used in multiple articles, which limited the ability to precisely compare findings.

##### Outcome

Weight was the most common outcome measured in the RCTs. Seven trials measured weight at follow-up,^44–51^ while fat mass and lean mass were measured in 4,^45,48–50^ and BMI^45,49,50^ in 3. Waist circumference was measured in a single study.^49^ Intervention durations were 12 weeks,^44,46,51^ 16 weeks,^49^ six months,^48^ and two years.^45,47,50^

The most common eligible outcomes in the PCS were measures of body composition. Ten articles examined waist circumference or abdominal obesity,^52,54,65,72,74,76–79^ 4 measured fat mass, and 2 measured lean mass. Risk of obesity was most frequently measured using continuous weight or BMI,^53,55,59,60,64,76,77,79^ though 4 studies looked at BMI cutoffs of overweight or obesity.^54,63,64,70^ Only one PCS had a follow-up period shorter than 1 year.^59^ Most had follow-up periods of 5 to 10 years, and 1 study extended beyond fifteen years. One study utilized self-reported outcome data;^53^ all others used data measured by trained study staffor health professionals.

#### Synthesis of the evidence

Due to the impact of energy intake on the relationship between milk consumption and outcomes of body composition and risk of obesity, studies were grouped by whether or not they accounted for TEI during the synthesis discussions. The studies in this body of evidence are summarized in Table 19, with their risk of bias assessments summarized in Table 20 and Table 21.

The 8 RCT articles representing 7 independent trials tended to find a null effect of a milk intervention on the outcomes of body composition and risk of obesity. In the 3 trials where energy intake was accounted for, Malaysian study found no difference between a skim milk intervention compared to the usual diet control on outcomes of fat mass, lean mass, or weight at the two-year follow up.^45^ Longer-term follow up from that same trial found an increase in lean body mass at 45 months in the intervention participants who remained compared to the control participants, though attrition had reached >30%. Between-group differences for BMI, weight, and fat mass remained non-significant.^50^ Rosado and Wagner both compared a milk intervention plus energy-restricted diet to an energy-restricted diet alone and found no between-group differences in waist circumference, fat mass, lean mass, weight or BMI^49^ or weight change^51^ Wagner did find a significant difference in fat mass at 12 weeks, with the milk intervention group losing less body fat than the control group.

For trials in which energy was not accounted for, 1 showed significantly greater weight gain in the intervention group compared to a usual diet control at 12 weeks,^44^ 1 showed an increase in weight at 18 months but not at 6, 12, or 24 months^47^, and the third showed no difference in weight at six months.^48^ Maersk also looked at lean mass and fat mass and found no difference between groups. Chiang focused on older adults with sarcopenia and found no impact of the intervention on fat mass, lean mass, BMI, or weight; and as mentioned earlier, was deprioritized in the synthesis due to the substantial differences in study purpose and population. Though RCT findings were somewhat mixed, accounting for energy intake in the study design suggested that detrimental relationships between milk intake and outcomes of body composition and risk of obesity may be driven by an unadjusted increase in energy intake rather than the milk itself.

The PCS showed a similar pattern, with most studies finding a null association between total milk intake and measures of body composition and risk of obesity. For articles that adjusted for TEI, 11 of 13 found a null association for most or all outcomes examined. The direction of association for the significant findings was mixed. One study found a detrimental association between increased milk intake and increased weight and BMI across 12 years of follow up; that same study found no association between milk intake and weight change, BMI change, waist circumference, or weight-to-height ratio across the follow-up period.^77^ Another study stratified by sex and race and found no associations for obesity incidence for the total sample and subgroups but decreased incidence of central obesity in men, increased incidence of central obesity in white participants, and no association in the total sample, women, or Black participants.^54^ Two others found a beneficial association between increased milk intake and decreased waist circumference^72^ and abdominal obesity.^74^

For PCS that did not adjust for energy intake, all but one found exclusively null associations across outcomes of weight, BMI, lean mass, fat mass, and incident obesity. The one exception stratified results by sex and found that increased milk intake was associated with increased incident obesity and BMI change over six years in men but not in women.^64^

Across all PCS, the majority of findings were null, and the few beneficial associations between milk and body composition and risk of obesity were only found in studies adjusting for energy intake. Detrimental associations were also few in number and were found in both studies that did and did not adjust for energy intake. Findings did not appear to vary by exposure definition, sample size, or duration of follow-up.

#### Conclusion statement and grade: Total milk

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement based on their review of the evidence to answer the question on dairy milk and milk alternative consumption and body composition and risk of obesity in adults. The conclusion statement and grade specific to total milk consumption by adults is documented below in Table 9.

Table 9 Conclusion statement and grade for total milk and body composition and risk of obesity in adults

Conclusion Statement | Total milk consumption by adults and older adults is not associated with measures of body composition or risk of obesity. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 8 RCT, 17 PCS
Consistency | Some concerns with inconsistency in the direction of results
Precision | Some concerns with precision due to small sample sizes and varying metrics
Risk of bias | Some concerns with risk of bias due to inadequate randomization, confounding, and missing data
Directness | Few concerns with directness
Generalizability | Substantial concerns with generalizability to the US population due to lack of data on race and/or ethnicity

##### Assessment of the evidence: Total milk for total milk consumption and body composition and risk of obesity in adults

The body of evidence underlying the conclusion statement on total milk consumption by adults consisted of 8 RCT and 17 PCS articles. The strength of evidence was graded using the five grading elements detailed below. While the literature search was comprehensive, a search of the gray literature was not done, which may increase the possibility of publication bias. However, the body of evidence includes both large and small studies, including small studies with null findings, so there is less concern of publication bias.

###### Consistency

Findings across studies looking at total milk consumption tended to be consistent, with most studies finding a null association with the outcomes of body composition and risk of obesity in adults. There were some significant findings in both the RCT and the PCS, and those findings were inconsistent in direction.

###### Precision

Most studies had large sample sizes, but two RCT were smaller and potentially underpowered.

###### Risk of bias

Risk of bias was commonly increased due to lack of adequate description of the randomization process in RCT and lack of accounting for key confounders and missing data in the PCS (Table 20 & Table 21).

###### Directness

All trials were designed to address milk intake and body composition or risk of obesity. Though the PCS were often broader in scope, there were no identified concerns with directness.

###### Generalizability

Generalizability was substantially impacted by the lack of data on race and/or ethnicity in at least half of the trials and lack of diversity in RCT that did report those data. The PCS were more geographically diverse, but the studies that reported race and/or ethnicity data or SEP were still very limited in diversity. Data stratifications by these variables were not available to determine if results generalized across groups.

### Milk by fat content

#### Description of the evidence

##### Population

Fourteen PCS examined milk consumption by fat content. Six were conducted in the U.S., three in Spain, two in Sweden, and one each in Canada, Denmark, and England. Sample sizes ranged from N=248 to N=124,988. Average participant age ranged from 25 to 67y. No studies exclusively enrolled older adults. Three cohorts exclusively enrolled female participants,^53,71,73^ and one enrolled only men.^62^

Multiple cohorts were represented by more than one article. The Nurses’ Health Study data were used in four articles,^53,68,69,75^ the Health Professionals Follow-Up Study in three,^68,69,75^ and secondary analyses from PREDIMED in two articles.^52,66^

Data on race and/or ethnicity were provided for 5 articles, five of which were predominantly white. The sixth cohort reported roughly half Black participants and half white. Data on SEP were presented for all but 4 cohorts. Occupation reflected large representation of health professionals, though 1 cohort consisted of a predominantly lower-SEP sample.^62^ Prevalence of overweight and obesity across cohorts tended to correspond with broader population rates.

##### Intervention/Exposure

There were no trials directly comparing the effects of milks by different fat content on body composition or risk of obesity in adults. However, 14 PCS examined intake of stratified by fat content. Three of these articles also examined total milk intake and are included in both bodies of evidence.^52,53,77^ There was less variability in how the different milk fat amounts were stratified in the adult evidence. Nine articles grouped lower-fat milks together (skim, 1%, and 2%) and whole milk separately. The remaining articles grouped low-fat and high-fat milk separately without providing specific definitions of those groups or the fat levels within. Intake was measured using an FFQ in 10 articles, a short questionnaire in three, and a three-day dietary record in one.

##### Comparator

For milk by fat content, 10 articles looked at continuous intake within each milk type. A small number of articles examined categorical intake, and those categories tended to be either tertiles of intake at a single time point or change in intake across time.

##### Outcome

Weight was the most commonly measured outcome in the PCS examining milk by fat content. Eight articles measured weight, while 2 measured BMI,^61,77^ and 1 measured prevalence of overweight/obesity at follow up.^71^ Measures of body composition were also frequently included, with 6 articles measuring waist circumference or abdominal obesity and one study measuring fat mass.77 All cohorts were followed for at least 1 year, and many were followed for more than 5 years. This body of evidence relied more heavily on self-reported outcome data than the evidence on total milk consumption. Six of the 14 PCS collected self-report height and weight data,^53,68,69,71,73,75^ while the remaining 8 studies used trained study personnel to measure the outcomes of interest.^52,56–58,61,62,66,77^

#### Synthesis of the evidence

Due to the impact of energy intake on the relationship between milk consumption and outcomes of body composition and risk of obesity, studies were grouped by whether or not they accounted for TEI during the synthesis discussions. The studies in this body of evidence are summarized in Table 19, with their risk of bias assessments summarized in Table 21.

There were no trials directly assessing the effect of different fat content in milk on the outcomes of body composition and risk of obesity in adults. Associations examined in the 14 PCS were highly variable in significance and direction. Roughly half of the associations across studies were null, while the remaining half were split between beneficial and detrimental associations between milk by fat content and the outcomes of interest. Energy intake was adjusted for in roughly half of the studies and did not appear to impact the distribution of results.

Weight was the most frequently assessed outcome, and BMI was concurrently measured in multiple cohorts: three articles found a null association with intake of different milk types and weight over time and five found a mix of null and significant findings depending on milk fat level. Of those with mixed findings, 1 found decreased odds of substantial weight gain over time with high intake of whole milk over time compared to low intake for the full sample and for women, specifically; but the association was not significant for men or for other milk types.^73^ Another study conversely found greater whole milk intake was associated with increased weight and BMI change but not absolute weight or BMI. Low-fat milk was associated with higher absolute weight and BMI but not change in any outcome.^77^ Two PCS examined the same cohorts and found different results with one associating low-fat milk with increased weight in one of the 2 female cohorts but not the second female cohort, the male cohort or other types of milk;^68^ while the other found no significant findings except when stratifying by BMI where they found increased weight for whole milk and decreased weight for low-fat milk in the male cohort only.^69^ The fifth PCS with mixed findings showed a significant relationship between increased low-fat milk intake and weight but only when adjusting for glycemic index; the relationship was non-significant otherwise, and no findings were significant for whole milk.

Measures of body composition were reported in 6 articles with inconsistent results. Three found no significant relationship between milk by fat level and waist circumference or abdominal obesity. One study associated whole milk intake with higher waist circumference, but only for the middle category of intake and only in women; there was no linear relationship with whole milk, no relationship at all with low-fat milk, and no relationship with either milk intake and abdominal obesity.^58^ In another, whole milk was associated with lower absolute waist circumference but not change in waist circumference, and low-fat milk was increased body fat percentage at follow up.^77^ And in the final PCS, whole milk was associated with decreased incidence of central obesity.^62^

Studies examining milk by fat content and its relationship with body composition or risk of obesity in adults found highly variable and inconsistent results, occasionally across the same cohorts. The variation in exposure definition across studies also contributed to difficulty drawing a conclusion since not all studies categorized milk fat in the same way.

#### Conclusion statement and grade: Milk by fat content

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement based on their review of the evidence to answer the question on dairy milk and milk alternative consumption and body composition and risk of obesity in adults. The conclusion statement and grade specific to milk by fat content in adults is documented below in Table 10.

Table 10 Conclusion statement and grade for milk by fat content and body composition and risk of obesity in adults

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of milk with different fat content by adults and older adults and body composition and risk of obesity because of substantial concerns with directness, consistency, and an absence of trial data in the body of evidence.
Grade | Grade Not Assignable
Body of Evidence | 14 PCS
Rationale | - There were no eligible trials examining milk by fat content in adults; - Findings for higher-fat milk intake were substantially mixed, with studies finding negative, positive, and null associations; - Multiple studies showed no association, or the direction of the association was difficult to interpret; - Exposure definition and comparators varied across studies (e.g., “Low-fat milk” defined as skim and 1% or skim, 1%, and 2%)

### Milk by sweetener content

No eligible studies were found examining milk by sweetener content in adults or older adults.

#### Conclusion statement and grade: Milk by sweetener content

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement based on their review of the evidence to answer the question on dairy milk and milk alternative consumption and body composition and risk of obesity in adults. The conclusion statement and grade specific to milk by sweetener content in adults is documented below in Table 11.

Table 11 Conclusion statement and grade for milk by sweetener content and body composition and risk of obesity in adults

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of sweetened milk by adults and older adults and body composition and risk of obesity because there is no evidence available.
Grade | Grade Not Assignable
Body of Evidence | 0 studies
Rationale | No articles met the inclusion criteria

### Milk alternative

#### Description of the evidence

##### Population

The single RCT examining milk alternatives was conducted in Taiwan and enrolled an 80% male sample of 36 older adults with sarcopenia. No data on race and/or ethnicity or SEP were provided.

##### Intervention/Exposure

The intervention included consuming 400 mL/d of soymilk combined with mild resistance exercise over 12 weeks.

##### Comparator

The RCT also had a dairy milk intervention group, both of which were compared to a group that received an equal amount of water each day. All groups received the same resistance exercise training in addition to the beverage.

##### Outcome

Fat mass, lean mass, BMI, and weight were measured at baseline and the end of the 12-week intervention.^46^

#### Synthesis of the evidence

The RCT examining soymilk intake compared to dairy milk and a water intake control found no significant between-group differences for any outcome (fat mass, lean mass, BMI, and weight at baseline) after 12 weeks.

#### Conclusion statement and grade: Milk alternatives

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement based on their review of the evidence to answer the question on dairy milk and milk alternative consumption and body composition and risk of obesity in adults. The conclusion statement and grade specific to milk alternatives is documented below in Table 12.

Table 12 Conclusion statement and grade for milk alternatives and body composition and risk of obesity in adults

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between consumption of milk alternatives by adults and older adults and body composition and risk of obesity because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 1 RCT
Rationale | There was only one eligible study examining milk alternative consumption and body composition and risk of obesity in adults.

##### Mendelian randomization studies

The Committee decided to summarize the of findings from eligible Mendelian randomization (MR) studies examining milk intake and growth, body composition, or risk of obesity, but not include them in the synthesis due to the methodological limitations of the study design in nutrition research. In brief, one sourced data from a combined U.S./U.K study, another was conducted in Denmark, one in Taiwan, and the fourth study did not report the cohort’s country of origin. Cohorts tended to be large, ranging from 10,000 to 404,648. Three of the four studies used the same genetic marker (rs4988235), which predicts lactase persistence or lactose intolerance, to predict milk intake. The fourth used a different SNP in linkage disequilibrium with another lactase persistence marker (rs375468). Milk intake tended to be directly measured in sub-samples of the cohorts studied. All four studies examined BMI or risk of overweight/obesity, and two also examined waist circumference or waist-to-hip ratio. Findings across MR studies were inconsistent. Two studies found an association between genetically-predicted milk intake and greater BMI or adiposity^80,81^, one study found an inverse relationship where genetically-predicted milk intake associated with lower BMI,^82^ and the fourth study found no significant relationship between the two.^83^

## Individuals during pregnancy and postpartum

### Description of the evidence

Two PCS were eligible for inclusion, both in individuals during pregnancy. Evidence for this population is summarized in Table 22, with risk of bias assessments summarized in Table 23. The studies were conducted in Iceland^84^ and Puerto Rico.^85^ Guilloty et al^85^ studied 160 Puerto Rican individuals with an average age of 27 years, 40% of whom had SEP below the poverty threshold. 44% had pre-pregnancy overweight or obesity. They assessed milk intake between weeks 20 and 28 of pregnancy using an FFQ of habitual intake over the previous year and examined the association of categorical intake frequency (<1 x/d, ≥1 x/d) with excessive, appropriate, and inadequate total gestational weight gain (GWG).

Olaffsdottir et al^84^ studied 406 Caucasian individuals who were 28 years of age, on average; 39% had pre-pregnancy overweight or obesity. No data were reported on SEP. They used a lifestyle questionnaire to assess milk intake during early (11–15 weeks) and late (34–37 weeks) pregnancy and asked participants to compare that intake to their usual intake before pregnancy. Those who drank more milk during either pregnancy time point were compared to those who did not change their habitual intake. GWG was also assessed by adequacy in this PCS.

### Synthesis of the evidence

Guilloty et al^85^ found no significant relationship between milk intake during pregnancy and gestational weight gain adequacy. Olafsdottir et al^84^ also found no significant relationship between drinking more milk early in pregnancy compared to pre-pregnancy and adequacy of gestational weight gain. For individuals drinking more milk late in pregnancy compared to pre-pregnancy, there was a positive association with optimal and excessiv GWG compared to suboptimal GWG. This relationship remained when comparing combined suboptimal and optimal GWG groups to those with excessive GWG.

Due to the substantial variation in how the two studies examined the exposure and the inconsistency in their findings, no conclusion could be drawn for this population.

### Conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee developed conclusion statements to address the relationshi between dairy milk and milk alternative consumption by individuals during pregnancy and postpartum and the outcomes of gestational weight gain and postpartum weight change, respectively (Table 13 and Table 14).

Table 13 Conclusion statements and grades for dairy milk and milk alternative consumption by individuals during pregnancy and gestational weight gain

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between milk consumption during pregnancy and adequacy of gestational weight gain because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 2 PCS
Rationale | Studies varied substantially on exposure definition and direction of findings

Table 14 Conclusion statement, grade for dairy milk and milk alternative consumption by individuals during postpartum and postpartum weight change

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between milk consumption during postpartum and postpartum weight change because there is no evidence available.
Grade | Grade Not Assignable
Body of Evidence | 0 studies
Rationale | No articles met the inclusion criteria