# Plain language Summary

### What is the question?

The question is: What is the relationship between dairy milk and milk alternative consumption and growth, body composition, and risk of obesity? The populations of interest for this question include children and adolescents, adults and older adults, and individuals during pregnancy and postpartum.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025–2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated an existing review that was conducted by the 2020 Dietary Guidelines Advisory Committee.

### What is the answer to the question?

#### Children and adolescents

- Total milk consumption by younger children may be associated with favorable growth and body composition, and lower risk of obesity during childhood. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between total milk consumption by older children and adolescents and growth, body composition, and risk of obesity because of substantial concerns with directness, consistency, and risk of bias in the body of evidence.
- Consumption of higher-fat dairy milk compared to lower-fat dairy milk by younger children may be associated with favorable growth and body composition, and lower risk of obesity during childhood. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between consumption of milk with different fat content by older children and adolescents and growth, body composition, and risk of obesity because of substantial concerns with consistency, quantity, and risk of bias in the body of evidence.
- A conclusion statement cannot be drawn about the relationship between consumption of sweetened milk by younger children and growth, body composition, and risk of obesity because there is no evidence available.
- There may not be a relationship between consumption of sweetened milk by older children and adolescents and growth, body composition, and risk of obesity. This conclusion statement is based on evidence graded as limited.
- A conclusion statement cannot be drawn about the relationship between consumption of milk alternatives by children and adolescents and growth, body composition, and risk of obesity because there is not enough evidence available.

#### Adults and older adults

- Total milk consumption by adults and older adults is not associated with measures of body composition or risk of obesity. This conclusion statement is based on evidence graded as moderate.
- A conclusion statement cannot be drawn about the relationship between consumption of milk with different fat content by adults and older adults and body composition and risk of obesity because of substantial concerns with directness, consistency, and an absence of trial data in the body of evidence.
- A conclusion statement cannot be drawn about the relationship between consumption of sweetened milk by adults and older adults and body composition and risk of obesity because there is no evidence available.
- A conclusion statement cannot be drawn about the relationship between consumption of milk alternatives by adults and older adults and body composition and risk of obesity because there is not enough evidence available.

#### Individuals during pregnancy and postpartum

- A conclusion statement cannot be drawn about the relationship between milk consumption during pregnancy and adequacy of gestational weight gain because there is not enough evidence available.
- A conclusion statement cannot be drawn about the relationship between milk consumption during postpartum and postpartum weight change because there is no evidence available.

### How up-to-date is this systematic review?

Conclusion statements from this review are based on articles published between January 2000 and May 2023.